# Appendix 1 Abbreviations

Table A 1 List of abbreviations
Abbreviation: Full name
BMI: Body Mass Index
DASH: Dietary Approaches to Stop Hypertension
DEXA: Dual X-ray Absorptiometry
FFQ: Food Frequency Questionnaire
HHS: United States Department of Health and Human Services
IOM: Institute of Medicine
NESR: Nutrition Evidence Systematic Review
PCS: Prospective Cohort Study
RCT: Randomized Controlled Trial
USDA: United States Department of Agriculture