# References of the articles included in the systematic review

1 Affenito SG, Thompson DR, Barton BA, Breakfast consumption by African-American and white adolescent girls correlates positively with calcium and fiber intake and negatively with body mass index. J Am Diet Assoc. 2005;105(6):938–945 doi:10.1016/j.jada.2005.03.003.15942545
2 Albertson AM, Franko DL, Thompson D, Longitudinal patterns of breakfast eating in black and white adolescent girls. Obesity (Silver Spring). 2007;15(9):2282–2292 doi:10.1038/oby.2007.271.17890497
3 Bajerska J, Chmurzynska A, Muzsik-Kazimierska A, Determinants favoring weight regain after weight-loss therapy among postmenopausal women. Sci Rep. 2020;10(1):17713 doi:10.1038/s41598-020-74302-7.33077809
4 Barton BA, Eldridge AL, Thompson D, The relationship of breakfast and cereal consumption to nutrient intake and body mass index: the National Heart, Lung, and Blood Institute Growth and Health Study. J Am Diet Assoc. 2005;105(9):1383–1389 doi:10.1016/j.jada.2005.06.003.16129079
5 Bel-Serrat S, Heinen MM, Mehegan J, Predictors of weight status in school-aged children: a prospective cohort study. Eur J Clin Nutr. 2019;73(9):1299–1306 doi:10.1038/s41430-018-0359-8.30446761
6 Berkey CS, Rockett HR, Gillman MW, Field AE, Colditz GA. Longitudinal study of skipping breakfast and weight change in adolescents. Int J Obes Relat Metab Disord. 2003;27(10):1258–1266 doi:10.1038/sj.ijo.0802402.14513075
7 Brophy S, Cooksey R, Gravenor MB, Risk factors for childhood obesity at age 5: analysis of the millennium cohort study. BMC Public Health. 2009;9:467 doi:10.1186/1471-2458-9-467.20015353
8 Cayres SU, Urban JB, Fernandes RA. Physical Activity and Skipping Breakfast Have Independent Effects on Body Fatness Among Adolescents. J Pediatr Gastroenterol Nutr. 2018;67(5):666–670 doi:10.1097/MPG.0000000000002081.29952827
9 Crossman A, Anne Sullivan D, Benin M. The family environment and American adolescents' risk of obesity as young adults. Soc Sci Med. 2006;63(9):2255–2267 doi:10.1016/j.socscimed.2006.05.027.16828216
10 de Winter AF, Visser L, Verhulst FC, Vollebergh WA, Reijneveld SA. Longitudinal patterns and predictors of multiple health risk behaviors among adolescents: The TRAILS study. Prev Med. 2016;84:76–82 doi:10.1016/j.ypmed.2015.11.028.26656404
11 Dhurandhar EJ, Dawson J, Alcorn A, The effectiveness of breakfast recommendations on weight loss: a randomized controlled trial. Am J Clin Nutr. 2014;100(2):507–513 doi:10.3945/ajcn.114.089573.24898236
12 Dolin CD, Gross RS, Deierlein AL, Predictors of Gestational Weight Gain in a Low-Income Hispanic Population: Sociodemographic Characteristics, Health Behaviors, and Psychosocial Stressors. Int J Environ Res Public Health. 2020;17(1) doi:10.3390/ijerph17010352.
13 Drenowatz C, Kobel S, Kettner S, Correlates of weight gain in German children attending elementary school. Prev Med. 2013;57(4):310–314 doi:10.1016/j.ypmed.2013.06.004.23769901
14 Elahy V, Jiang L, Lee S, Odegaard AO. A hypothetical intervention of the timing of dietary intake on weight and body composition after initial weight loss. Obesity (Silver Spring). 2023;31(4):1095–1107 doi:10.1002/oby.23688.36863748
15 Elgar FJ, Roberts C, Moore L, Tudor-Smith C. Sedentary behaviour, physical activity and weight problems in adolescents in Wales. Public Health. 2005;119(6):518–524 doi:10.1016/j.puhe.2004.10.011.15826893
16 Gingras V, Rifas-Shiman SL, Taveras EM, Oken E, Hivert MF. Dietary behaviors throughout childhood are associated with adiposity and estimated insulin resistance in early adolescence: a longitudinal study. Int J Behav Nutr Phys Act. 2018;15(1):129 doi:10.1186/s12966-018-0759-0.30558613
17 Goff LM, Huang P, Silva MJ, Associations of dietary intake with cardiometabolic risk in a multiethnic cohort: a longitudinal analysis of the Determinants of Adolescence, now young Adults, Social well-being and Health (DASH) study. Br J Nutr. 2019;121(9):1069–1079 doi:10.1017/S0007114519000291.30764887
18 Goto M, Kiyohara K, Kawamura T. Lifestyle risk factors for overweight in Japanese male college students. Public Health Nutr. 2010;13(10):1575–1580 doi:10.1017/S1368980009992813.20025829
19 Guinter MA, Park YM, Steck SE, Sandler DP. Day-to-day regularity in breakfast consumption is associated with weight status in a prospective cohort of women. Int J Obes (Lond). 2020;44(1):186–194 doi:10.1038/s41366-019-0356-6.30926951
20 Haerens L, Vereecken C, Maes L, De Bourdeaudhuij I. Relationship of physical activity and dietary habits with body mass index in the transition from childhood to adolescence: a 4-year longitudinal study. Public Health Nutr. 2010;13(10A):1722–1728 doi:10.1017/S1368980010002284.20883572
21 Haines J, Neumark-Sztainer D, Wall M, Story M. Personal, behavioral, and environmental risk and protective factors for adolescent overweight. Obesity (Silver Spring). 2007;15(11):2748–2760 doi:10.1038/oby.2007.327.18070766
22 Hassan BK, Cunha DB, da Veiga GV, Pereira RA, Hoffman DJ, Sichieri R. Breakfast Consumption, Family Breakfast, and Adiposity Trajectory in Adolescence-The Adolescent Nutritional Assessment Longitudinal Cohort Study. J Acad Nutr Diet. 2019;119(6):944–956 doi:10.1016/j.jand.2018.11.014.30745069
23 Ikeda N, Nishi N. First incidence and associated factors of overweight and obesity from preschool to primary school: longitudinal analysis of a national cohort in Japan. Int J Obes (Lond). 2019;43(4):751–760 doi:10.1038/s41366-018-0307-7.30659255
24 Jeans MR, Vandyousefi S, Landry MJ, Breakfast Consumption May Improve Fasting Insulin, HOMA-IR, and HbA1c Levels in Predominately Low-Income, Hispanic Children 7–12 Years of Age. Nutrients. 2022;14(11) doi:10.3390/nu14112320.
25 Kelly Y, Patalay P, Montgomery S, Sacker A. BMI Development and Early Adolescent Psychosocial Well-Being: UK Millennium Cohort Study. Pediatrics. 2016;138(6) doi:10.1542/peds.2016-0967.
26 Kesztyus D, Lauer R, Kesztyus T, Kilian R, Steinacker JM, Join the Healthy Boat" Study G. Costs and effects of a state-wide health promotion program in primary schools in Germany - the Baden-Wurttemberg Study: A cluster-randomized, controlled trial. PLoS One. 2017;12(2):e0172332 doi:10.1371/journal.pone.0172332.28222101
27 Kesztyus D, Traub M, Lauer R, Kesztyus T, Steinacker JM. Correlates of longitudinal changes in the waist-to-height ratio of primary school children: Implications for prevention. Prev Med Rep. 2016;3:1–6 doi:10.1016/j.pmedr.2015.11.005.26844178
28 Kim HS, Jung SJ, Mun EG, Kim MS, Cho SM, Cha YS. Effects of a Rice-Based Diet in Korean Adolescents Who Habitually Skip Breakfast: A Randomized, Parallel Group Clinical Trial. Nutrients. 2021;13(3) doi:10.3390/nu13030853.
29 Kito K, Kuriyama A, Takahashi Y, Nakayama T. Impacts of skipping breakfast and late dinner on the incidence of being overweight: a 3-year retrospective cohort study of men aged 20–49 years. J Hum Nutr Diet. 2019;32(3):349–355 doi:10.1111/jhn.12640.30821869
30 Kunaratnam K, Halaki M, Wen LM, Baur LA, Flood VM. Tracking Preschoolers' Lifestyle Behaviors and Testing Maternal Sociodemographics and BMI in Predicting Child Obesity Risk. J Nutr. 2020;150(12):3068–3074 doi:10.1093/jn/nxaa292.33096560
31 Kupers LK, de Pijper JJ, Sauer PJ, Stolk RP, Corpeleijn E. Skipping breakfast and overweight in 2- and 5-year-old Dutch children-the GECKO Drenthe cohort. Int J Obes (Lond). 2014;38(4):569–571 doi:10.1038/ijo.2013.194.24158122
32 LaRose JG, Neiberg RH, Evans EW, Dietary outcomes within the study of novel approaches to weight gain prevention (SNAP) randomized controlled trial. Int J Behav Nutr Phys Act. 2019;16(1):14 doi:10.1186/s12966-019-0771-z.30704533
33 Larson N, Chen Y, Wall M, Winkler MR, Goldschmidt AB, Neumark-Sztainer D. Personal, behavioral, and environmental predictors of healthy weight maintenance during the transition to adulthood. Prev Med. 2018;113:80–90 doi:10.1016/j.ypmed.2018.04.027.29727637
34 Laska MN, Murray DM, Lytle LA, Harnack LJ. Longitudinal associations between key dietary behaviors and weight gain over time: transitions through the adolescent years. Obesity (Silver Spring). 2012;20(1):118–125 doi:10.1038/oby.2011.179.21701567
35 Lee EY, Kang B, Yang Y, Study Time after School and Habitual Eating Are Associated with Risk for Obesity among Overweight Korean Children: A Prospective Study. Obes Facts. 2018;11(1):46–55 doi:10.1159/000486132.29408816
36 Lee H, Harris KM, Gordon-Larsen P. Life Course Perspectives on the Links Between Poverty and Obesity During the Transition to Young Adulthood. Popul Res Policy Rev. 2009;28(4):505–532 doi:10.1007/s11113-008-9115-4.20161083
37 Leidy HJ, Hoertel HA, Douglas SM, Higgins KA, Shafer RS. A high-protein breakfast prevents body fat gain, through reductions in daily intake and hunger, in "Breakfast skipping" adolescents. Obesity. 2015;23(9):1761–1764 doi:10.1002/oby.21185.26239831
38 Libuy N, Bann D, Fitzsimons E. Inequalities in body mass index, diet and physical activity in the UK: Longitudinal evidence across childhood and adolescence. SSM Popul Health. 2021;16:100978 doi:10.1016/j.ssmph.2021.100978.34950761
39 Liechty JM, Lee MJ. Body size estimation and other psychosocial risk factors for obesity onset among US adolescents: findings from a longitudinal population level study. Int J Obes (Lond). 2015;39(4):601–607 doi:10.1038/ijo.2014.191.25370575
40 Lipsky LM, Haynie DL, Liu D, Trajectories of eating behaviors in a nationally representative cohort of U.S. adolescents during the transition to young adulthood. Int J Behav Nutr Phys Act. 2015;12:138 doi:10.1186/s12966-015-0298-x.26537771
41 MacFarlane A, Cleland V, Crawford D, Campbell K, Timperio A. Longitudinal examination of the family food environment and weight status among children. Int J Pediatr Obes. 2009;4(4):343–352 doi:10.3109/17477160902846211.19922051
42 Martinez CF, Ortiz-Panozo E, Mattei J, Campos H, Flores-Aldana M, Lajous M. Breakfast Frequency Is Inversely Associated with Weight Gain in a Cohort of Mexican Women. J Nutr. 2021;151(2):405–411 doi:10.1093/jn/nxaa367.33382425
43 Megson M, Wing R, Leahey TM. Effects of breakfast eating and eating frequency on body mass index and weight loss outcomes in adults enrolled in an obesity treatment program. J Behav Med. 2017;40(4):595–601 doi:10.1007/s10865-017-9828-0.28110468
44 Merten MJ, Williams AL, Shriver LH. Breakfast consumption in adolescence and young adulthood: parental presence, community context, and obesity. J Am Diet Assoc. 2009;109(8):1384–1391 doi:10.1016/j.jada.2009.05.008.19631044
45 Narla A, Rehkopf DH. Novel ranking of protective and risk factors for adolescent adiposity in US females. Obes Sci Pract. 2019;5(2):177–186 doi:10.1002/osp4.323.31019735
46 Neumark-Sztainer DR, Wall MM, Haines JI, Story MT, Sherwood NE, van den Berg PA. Shared risk and protective factors for overweight and disordered eating in adolescents. Am J Prev Med. 2007;33(5):359–369 doi:10.1016/j.amepre.2007.07.031.17950400
47 Niemeier HM, Raynor HA, Lloyd-Richardson EE, Rogers ML, Wing RR. Fast food consumption and breakfast skipping: predictors of weight gain from adolescence to adulthood in a nationally representative sample. J Adolesc Health. 2006;39(6):842–849 doi:10.1016/j.jadohealth.2006.07.001.17116514
48 Nishiura C, Noguchi J, Hashimoto H. Dietary patterns only partially explain the effect of short sleep duration on the incidence of obesity. Sleep. 2010;33(6):753–757 doi:10.1093/sleep/33.6.753.20550015
49 Nooyens AC, Visscher TL, Schuit AJ, Effects of retirement on lifestyle in relation to changes in weight and waist circumference in Dutch men: a prospective study. Public Health Nutr. 2005;8(8):1266–1274 doi:10.1079/phn2005756.16372922
50 Odegaard AO, Jacobs DR, Jr., Steffen LM, Van Horn L, Ludwig DS, Pereira MA. Breakfast frequency and development of metabolic risk. Diabetes Care. 2013;36(10):3100–3106 doi:10.2337/dc13-0316.23775814
51 Okada C, Tabuchi T, Iso H. Association between skipping breakfast in parents and children and childhood overweight/obesity among children: a nationwide 10.5-year prospective study in Japan. Int J Obes (Lond). 2018;42(10):1724–1732 doi:10.1038/s41366-018-0066-5.29686380
52 Phelan S, Wing RR, Raynor HA, Dibello J, Nedeau K, Peng W. Holiday weight management by successful weight losers and normal weight individuals. J Consult Clin Psychol. 2008;76(3):442–448 doi:10.1037/0022-006X.76.3.442.18540737
53 Phelan S, Wyatt HR, Hill JO, Wing RR. Are the eating and exercise habits of successful weight losers changing? Obesity (Silver Spring). 2006;14(4):710–716 doi:10.1038/oby.2006.81.16741274
54 Quick V, Wall M, Larson N, Haines J, Neumark-Sztainer D. Personal, behavioral and socio-environmental predictors of overweight incidence in young adults: 10-yr longitudinal findings. Int J Behav Nutr Phys Act. 2013;10:37 doi:10.1186/1479-5868-10-37.23531253
55 Sakurai M, Yoshita K, Nakamura K, Skipping breakfast and 5-year changes in body mass index and waist circumference in Japanese men and women. Obes Sci Pract. 2017;3(2):162–170 doi:10.1002/osp4.106.28702211
56 Samano R, Martinez-Rojano H, Ortiz-Hernandez L, Dietary and Nutrient Intake, Eating Habits, and Its Association with Maternal Gestational Weight Gain and Offspring's Birth Weight in Pregnant Adolescents. Nutrients. 2022;14(21) doi:10.3390/nu14214545.
57 Seki T, Takeuchi M, Kawakami K. Eating and drinking habits and its association with obesity in Japanese healthy adults: retrospective longitudinal big data analysis using a health check-up database. Br J Nutr. 2021;126(10):1585–1591 doi:10.1017/S0007114521000179.33461638
58 Seum T, Meyrose AK, Rabel M, Schienkiewitz A, Ravens-Sieberer U. Pathways of Parental Education on Children's and Adolescent’s Body Mass Index: The Mediating Roles of Behavioral and Psychological Factors. Front Public Health. 2022;10:763789 doi:10.3389/fpubh.2022.763789.35321198
59 Shang X, Li Y, Xu H, Healthy breakfast habits and changes in obesity-related cardiometabolic markers in children: a longitudinal analysis. Eur J Clin Nutr. 2020;74(12):1685–1697 doi:10.1038/s41430-020-0614-7.32231225
60 Smith KJ, Gall SL, McNaughton SA, Blizzard L, Dwyer T, Venn AJ. Skipping breakfast: longitudinal associations with cardiometabolic risk factors in the Childhood Determinants of Adult Health Study. Am J Clin Nutr. 2010;92(6):1316–1325 doi:10.3945/ajcn.2010.30101.20926520
61 Smith KJ, Gall SL, McNaughton SA, Lifestyle behaviours associated with 5-year weight gain in a prospective cohort of Australian adults aged 26–36 years at baseline. BMC Public Health. 2017;17(1):54 doi:10.1186/s12889-016-3931-y.28068968
62 Suka M, Yamauchi T, Yanagisawa H. Lifestyle Changes and Weight Gain: A 2-Year Follow-up Study of Japanese Workers. J Occup Environ Med. 2020;62(7):e318–e327 doi:10.1097/JOM.0000000000001888.32730035
63 Timlin MT, Pereira MA, Story M, Neumark-Sztainer D. Breakfast eating and weight change in a 5-year prospective analysis of adolescents: Project EAT (Eating Among Teens). Pediatrics. 2008;121(3):e638–645 doi:10.1542/peds.2007-1035.18310183
64 Tin SP, Ho SY, Mak KH, Wan KL, Lam TH. Breakfast skipping and change in body mass index in young children. Int J Obes (Lond). 2011;35(7):899–906 doi:10.1038/ijo.2011.58.21448130
65 Tokumaru T, Toyama T, Hara A, Association between Unhealthy Dietary Habits and Proteinuria Onset in a Japanese General Population: A Retrospective Cohort Study. Nutrients. 2020;12(9) doi:10.3390/nu12092511.
66 Traub M, Lauer R, Kesztyus T, Skipping breakfast, overconsumption of soft drinks and screen media: longitudinal analysis of the combined influence on weight development in primary schoolchildren. BMC Public Health. 2018;18(1):363 doi:10.1186/s12889-018-5262-7.29548323
67 van der Heijden AA, Hu FB, Rimm EB, van Dam RM. A prospective study of breakfast consumption and weight gain among U.S. men. Obesity (Silver Spring). 2007;15(10):2463–2469 doi:10.1038/oby.2007.292.17925472
68 van Nassau F, Singh AS, Cerin E, The Dutch Obesity Intervention in Teenagers (DOiT) cluster controlled implementation trial: intervention effects and mediators and moderators of adiposity and energy balance-related behaviours. Int J Behav Nutr Phys Act. 2014;11:158 doi:10.1186/s12966-014-0158-0.25539582
69 Viner RM, Cole TJ. Who changes body mass between adolescence and adulthood? Factors predicting change in BMI between 16 year and 30 years in the 1970 British Birth Cohort. Int J Obes (Lond). 2006;30(9):1368–1374 doi:10.1038/sj.ijo.0803183.16552412
70 Wang S, Schwartz MB, Shebl FM, Read M, Henderson KE, Ickovics JR. School breakfast and body mass index: a longitudinal observational study of middle school students. Pediatr Obes. 2017;12(3):213–220 doi:10.1111/ijpo.12127.26989876
71 Wijtzes AI, Jansen W, Bouthoorn SH, Meal-Skipping Behaviors and Body Fat in 6-Year-Old Children. J Pediatr. 2016;168:118–125 e112 doi:10.1016/j.jpeds.2015.09.039.26520914
72 Wu CH, Lin CY, Hsieh YP, Dietary behaviors mediate the association between food insecurity and obesity among socioeconomically disadvantaged youth. Appetite. 2019;132:275–281 doi:10.1016/j.appet.2018.10.013.30327150
73 Yaguchi-Tanaka Y, Tabuchi T. Skipping Breakfast and Subsequent Overweight/Obesity in Children: A Nationwide Prospective Study of 2.5- to 13-year-old Children in Japan. J Epidemiol. 2021;31(7):417–425 doi:10.2188/jea.JE20200266.32655088
74 Yamamoto R, Tomi R, Shinzawa M, Associations of Skipping Breakfast, Lunch, and Dinner with Weight Gain and Overweight/Obesity in University Students: A Retrospective Cohort Study. Nutrients. 2021;13(1) doi:10.3390/nu13010271.
75 Zhang LJ, Cordeiro LS, Liu JH, Ma YS. The Association between Breakfast Skipping and Body Weight, Nutrient Intake, and Metabolic Measures among Participants with Metabolic Syndrome. Nutrients. 2017;9(4) doi:10.3390/nu9040384.
76 Barrington WE, Beresford SAA. Eating Occasions, Obesity and Related Behaviors in Working Adults: Does it Matter When You Snack? Nutrients. 2019;11(10) doi:10.3390/nu11102320.
77 Bes-Rastrollo M, Sanchez-Villegas A, Basterra-Gortari FJ, Nunez-Cordoba JM, Toledo E, Serrano-Martinez M. Prospective study of self-reported usual snacking and weight gain in a Mediterranean cohort: the SUN project. Clin Nutr. 2010;29(3):323–330 doi:10.1016/j.clnu.2009.08.017.19748710
78 Choi MJ, Kang H, Choi J. Risk Factors for Obesity in Five-Year-Old Children: Based on Korean National Health Insurance Service (NHIS) Data. Children (Basel). 2022;9(3) doi:10.3390/children9030314.
79 Francis LA, Lee Y, Birch LL. Parental weight status and girls' television viewing, snacking, and body mass indexes. Obes Res. 2003;11(1):143–151 doi:10.1038/oby.2003.23.12529497
80 Larsen SC, Heitmann BL. More Frequent Intake of Regular Meals and Less Frequent Snacking Are Weakly Associated with Lower Long-Term Gains in Body Mass Index and Fat Mass in Middle-Aged Men and Women. J Nutr. 2019;149(5):824–830 doi:10.1093/jn/nxy326.31034009
81 Lee HH, Park HA, Kang JH, Factors related to body mass index and body mass index change in korean children: preliminary results from the obesity and metabolic disorders cohort in childhood. Korean J Fam Med. 2012;33(3):134–143 doi:10.4082/kjfm.2012.33.3.134.22787535
82 Pimenta AM, Bes-Rastrollo M, Gea A, Snacking between main meals is associated with a higher risk of metabolic syndrome in a Mediterranean cohort: the SUN Project (Seguimiento Universidad de Navarra). Public Health Nutr. 2016;19(4):658–666 doi:10.1017/S1368980015001342.25958949
83 Poston WS, Haddock CK, Pinkston MM, Weight loss with meal replacement and meal replacement plus snacks: a randomized trial. Int J Obes (Lond). 2005;29(9):1107–1114 doi:10.1038/sj.ijo.0803007.15925955
84 Ritchie LD. Less frequent eating predicts greater BMI and waist circumference in female adolescents. Am J Clin Nutr. 2012;95(2):290–296 doi:10.3945/ajcn.111.016881.22218154
85 Yoshida J, Eguchi E, Nagaoka K, Ito T, Ogino K. Association of night eating habits with metabolic syndrome and its components: a longitudinal study. BMC Public Health. 2018;18(1):1366 doi:10.1186/s12889-018-6262-3.30537972
86 Arenaza L, Medrano M, Oses M, The Effect of a Family-Based Lifestyle Education Program on Dietary Habits, Hepatic Fat and Adiposity Markers in 8–12-Year-Old Children with Overweight/Obesity. Nutrients. 2020;12(5) doi:10.3390/nu12051443.
87 Bachman JL, Raynor HA. Effects of manipulating eating frequency during a behavioral weight loss intervention: a pilot randomized controlled trial. Obesity (Silver Spring). 2012;20(5):985–992 doi:10.1038/oby.2011.360.22173575
88 Bernabe-Ortiz A, Carrillo-Larco RM. Longitudinal association between food frequency and changes in body mass index: a prospective cohort study. BMJ Open. 2020;10(9):e037057 doi:10.1136/bmjopen-2020-037057.
89 Berteus Forslund H, Klingstrom S, Hagberg H, Londahl M, Torgerson JS, Lindroos AK. Should snacks be recommended in obesity treatment? A 1-year randomized clinical trial. Eur J Clin Nutr. 2008;62(11):1308–1317 doi:10.1038/sj.ejcn.1602860.17700649
90 Evans EW, Jacques PF, Dallal GE, Sacheck J, Must A. The role of eating frequency on relative weight in urban school-age children. Pediatr Obes. 2015;10(6):442–447 doi:10.1111/ijpo.12004.25565335
91 Georgiopoulos G, Karatzi K, Yannakoulia M, Eating frequency predicts changes in regional body fat distribution in healthy adults. QJM. 2017;110(11):729–734 doi:10.1093/qjmed/hcx120.29017004
92 Grangeiro ED, Trigueiro MS, Siais LO, Hypocaloric diet with lower meal frequency did not affect weight loss, body composition and insulin responsiveness, but improved lipid profile: a randomized clinical trial. Food Funct. 2021;12(24):12594–12605 doi:10.1039/d1fo00484k.34816273
93 Huseinovic E, Winkvist A, Bertz F, Forslund HB, Brekke HK. Eating frequency, energy intake and body weight during a successful weight loss trial in overweight and obese postpartum women. Eur J Clin Nutr. 2014;68(1):71–76 doi:10.1038/ejcn.2013.200.24193227
94 Juton C, Berruezo P, Torres S, Association between Meal Frequency and Weight Status in Spanish Children: A Prospective Cohort Study. Nutrients. 2023;15(4) doi:10.3390/nu15040870.
95 Loy SL, Cheung YB, Colega MT, Associations of Circadian Eating Pattern and Diet Quality with Substantial Postpartum Weight Retention. Nutrients. 2019;11(11) doi:10.3390/nu11112686.
96 Makarem N, Sears DD, St-Onge MP, Habitual Nightly Fasting Duration, Eating Timing, and Eating Frequency are Associated with Cardiometabolic Risk in Women. Nutrients. 2020;12(10) doi:10.3390/nu12103043.
97 Malaeb S, Harindhanavudhi T, Dietsche K, Time-Restricted Eating Alters Food Intake Patterns, as Prospectively Documented by a Smartphone Application. Nutrients. 2020;12(11) doi:10.3390/nu12113396.
98 Syrad H, Llewellyn CH, Johnson L, Meal size is a critical driver of weight gain in early childhood. Sci Rep. 2016;6:28368 doi:10.1038/srep28368.27321917
99 Taylor RW, Iosua E, Heath AM, Eating frequency in relation to BMI in very young children: a longitudinal analysis. Public Health Nutr. 2017;20(8):1372–1379 doi:10.1017/S1368980017000143.28238299
100 Thompson OM, Ballew C, Resnicow K, Dietary pattern as a predictor of change in BMI z-score among girls. Int J Obes (Lond). 2006;30(1):176–182 doi:10.1038/sj.ijo.0803072.16158084
101 Yildiran H, Mercanligil SM. Does increasing meal frequency improve weight loss and some biochemical parameters in overweight/obese females? Nutr Hosp. 2019;36(1):66–72 doi:10.20960/nh.2191.30836763
102 Hatami Zargaran Z, Salehi M, Heydari ST, Babajafari S. The Effects of 6 Isocaloric Meals on Body Weight, Lipid Profiles, Leptin, and Adiponectin in Overweight Subjects (BMI > 25). Int Cardiovasc Res J. 2014;8(2):52–56.24936481
103 Chu J, Ganson KT, Vittinghoff E, Weight Goals, Disordered Eating Behaviors, and BMI Trajectories in US Young Adults. J Gen Intern Med. 2021;36(9):2622–2630 doi:10.1007/s11606-021-06702-y.33876378
104 Field AE, Haines J, Rosner B, Willett WC. Weight-control behaviors and subsequent weight change among adolescents and young adult females. Am J Clin Nutr. 2010;91(1):147–153 doi:10.3945/ajcn.2009.28321.19889827
105 Franko DL, Striegel-Moore RH, Thompson D, The relationship between meal frequency and body mass index in black and white adolescent girls: more is less. Int J Obes (Lond). 2008;32(1):23–29 doi:10.1038/sj.ijo.0803654.17563764
106 Neumark-Sztainer D, Wall M, Story M, Standish AR. Dieting and unhealthy weight control behaviors during adolescence: associations with 10-year changes in body mass index. J Adolesc Health. 2012;50(1):80–86 doi:10.1016/j.jadohealth.2011.05.010.22188838
107 Stea TH, Vik FN, Bere E, Svendsen MV, Oellingrath IM. Meal pattern among Norwegian primary-school children and longitudinal associations between meal skipping and weight status. Public Health Nutr. 2015;18(2):286–291 doi:10.1017/S136898001400010X.24521714