# Summary of conclusion statements and grades

The 2025 Dietary Guidelines Advisory Committee answered the systematic review question, “What is the relationship between frequency of meals and/or snacking and growth, body composition, and risk of obesity?”, with the following conclusion statements.^*^ The grades reflect the strength of the evidence underlying the conclusion statements.

* A conclusion statement is carefully constructed, based on the evidence reviewed, to answer the systematic review question. A conclusion statement does not draw implications and should not be interpreted as dietary guidance.

### Children and adolescents

Regular breakfast consumption by children and adolescents may be associated with favorable outcomes related to growth, body composition, and/or lower risk of obesity. This conclusion statement is based on evidence graded as moderate. (Grade: Moderate)

Frequency of daily snacking during childhood may not be associated with outcomes related to growth, body composition, and/or risk of obesity. This conclusion statement is based on evidence graded as limited. (Grade: Limited)

Higher number of eating occasions per day during childhood may be associated with favorable outcomes related to growth, body composition, and/ or lower risk of obesity. This conclusion statement is based on evidence graded as limited. (Grade: Limited)

Meal frequency/skipping by children and adolescents may not be associated with outcomes related to risk of overweight or obesity. This conclusion statement is based on evidence graded as limited. (Grade: Limited)

A conclusion statement cannot be drawn about the relationship between meal frequency/skipping by children and adolescents and growth and body composition because there is not enough evidence available. (Grade: Grade Not Assignable)

### Adults and older adults

Breakfast skipping in adults and older adults is not associated with favorable outcomes related to body weight and composition and risk of obesity. This conclusion statement is based on evidence graded as limited. (Grade: Limited)

Overall snacking in adults may not be associated with outcomes related to body composition and risk of obesity. However, after dinner/evening snacking in adults may be associated with less favorable outcomes related to body composition and risk of obesity. This conclusion statement is based on evidence graded as limited. (Grade: Limited)

A conclusion statement cannot be drawn about the relationship between snacking in older adults and body composition and risk of obesity because there is not enough evidence available. (Grade: Grade Not Assignable)

Number of eating occasions per day in adults is not associated with outcomes related to change in body composition and weight. This conclusion statement is based on evidence graded as moderate. (Grade: Moderate)

A conclusion statement cannot be drawn about the relationship between number of eating occasions in older adults and body composition and risk of obesity because there is not enough evidence available. (Grade: Grade Not Assignable)

A conclusion statement cannot be drawn about the relationship between lunch or dinner frequency in adults and older adults and outcomes related to body composition and risk of obesity because of substantial concerns related to directness and generalizability in a small body of evidence. (Grade: Grade Not Assignable)

### Individuals during pregnancy or postpartum

A conclusion statement cannot be drawn about the relationship between frequency of meals and/or snacking during pregnancy and gestational weight gain because there is not enough evidence available. (Grade: Grade Not Assignable)

A conclusion statement cannot be drawn about the relationship between frequency of meals and/or snacking during postpartum and postpartum weight change because there is not enough evidence available. (Grade: Grade Not Assignable)

## Research recommendations

The Committee identified the following research recommendations that describe the research, data, and methodological advances that are needed to strengthen the body of evidence on frequency of meals and/or snacking and growth, body composition, and risk of obesity.

1. Develop definitions of eating occasion, meals, and snacks as well as frameworks and reporting standards to be used consistently in research in order to increase comparability across studies and aid in the development of guidance around this topic.
2. Develop and support prospective and/or experimental research that examines the relationship between frequency of meals and/or snacking and growth, body composition, and risk of obesity in all age groups, including older adults, which includes a target population reflective of the geographic, racial, and socioeconomic diversity in the U.S.
3. Include details about what foods were consumed and their quality by study participants when reporting results related to frequency of meals and/or snacking and growth, body composition, and risk of obesity.
4. Support research with funding from Federal and other funding agencies that provides information on types, frequency, timing, and size of meals and/or snacks in order to increase the accuracy and precision of the assessment of meal and snack frequency patterns and the ability to assess the combined and independent effects of frequency and timing of eating.
5. Provide consistency in the operational definition of frequency across studies when developing the comparisons to be examined in articles (e.g., categories of frequency comparisons vs. continuous frequency).
6. Explore all different meals and snack frequency patterns as a 24-hour eating behavior rather than isolating a meal or a snack and consider longer intervention period and follow-up.
7. Conduct studies that have enough follow up to understand the long-term impact of meals/snacks frequency patterns on energy intake.

Table 18 Evidence examining the relationship between breakfast in children and adolescents and growth, body composition, and risk of obesity^a^

Study and Population Characteristics | Intervention, Comparator, and Outcome(s) | Results | Study Limitations
Kim, 2021^28^; RCT-Parallel, South Korea; Baseline N=105, Analytic N=105 (ITT), 87 (PP), 81 (suitable meal compliance) (Attrition: 83% (PP), 77% (suitable meal compliance)); Study objective: To evaluate the positive effects of a rice-based breakfast in Korean adolescents who usually skip breakfast.; Participant characteristics at baseline: habitual meal skippers; - Age: 15.7 (0.2)y; - Female: 61%; - Race and/or ethnicity: NR, likely majority Asian; - Socioeconomic position: NR; - Anthropometry: BMI ~21 kg/m^2^; - Physical activity: ~2500 MET min/wk; - Smoking: NR; - TEI: ~1700 (500) kcal/d; NS between groups; - Habitual diet at baseline: All had breakfast <3 times/wk; Excluded from study or analysis: lost to follow-up; lack of compliance; usually consumed breakfast >3 times/wk; took medicines or health functional foods related to adolescent health factors >5 times/wk within 1mo before baseline; took OTC medicine or herbal medicine within 2wk prior to baseline or dietary supplements, probiotics, laxatives, dietary fiber, or vitamin preparations within 1wk before baseline | Intervention:; Rice-based breakfast vs. wheat-based breakfast vs. Control (usual habits, which was breakfast <3 times/wk); Rice and wheat breakfast were ~760kcal; Duration: 12wk; Compliance: 77% complied with meals; Outcomes and assessment methods:; - At baseline, 12wk follow-up; - Anthropometric parameters (weight, height, BMI) were measured using Inbody 720. Waist and hip circumference were measured by study personnel. | [underlined: Change in fat mass (kg) over 12wk], Mean (SD); Control: 0.5 (2.9); Rice: 0.3 (3.3); Wheat: 0.9 (2.1); p=0.017 (Control vs Wheat or Rice, p=NS); [underlined: Change in fat mass % over 12wk], Mean (SD); Control: −0.3 (2.1); Rice: −0.2 (3.4); Wheat: 0.1 (2.4); p=0.031 (Control vs. Wheat, p<0.05); [underlined: Change in lean body mass (g) over 12wk], Mean (SD); Control: 1.1 (2.4); Rice: 1.1 (4.9); Wheat: 1.8 (3.6) p=0.528; [underlined: Change in WC (cm) over 12wk], Mean (SD); Control: −1.7 (4.1); Rice: −0.49 (5.65); Wheat: 0.6 (3.9) p=0.467; [underlined: Change in waist:hip ratio over 12wk], Mean (SD); Control: 0.00 (0.04); Rice: 0.02 (0.03); Wheat: 0.02 (0.03) p=0.984; [underlined: Change in weight (kg) over 12wk], Mean (SD); Control: 1.8 (4.6); Rice: 1.3 (6.7); Wheat: 2.6 (5.1); p=0.034 (Control vs Wheat or Rice, p=NS); [underlined: Change in BMI (kg/m^2^) over 12wk], Mean (SD); Control: 0.4 (1.3); Rice: 0.3 (1.6); Wheat: 0.9 (1.4); p=0.023 (Control vs Wheat or Rice, p=NS); [underlined: Change in obesity rate (%)], Chi-square 8.93, p=0.411 | Model adjustments:; - TEI: no; Limitations:; - Methods for randomization and concealment; - Preregistered protocol (not accessible; - Multiple outcomes measured, but not all reported); Did not report compliance with breakfast skipping of the control group; Funding:; Agriculture Science & Technology Development Rural Development Administration, Republic of Korea Jeonbuk National University
OBSERVATIONAL STUDIES
Affenito, 2005^1^; PCS, NHLBI Growth and Health Study, U.S.; Analytic N=2,379; Study objective: To describe age- and race-related differences in breakfast consumption and to examine the association of breakfast intake with dietary calcium and fiber and body mass index; Participant characteristics at baseline: Black and White adolescent females; - Age: 9y; - Female: 100%; - Race and/or ethnicity: Non-Hispanic White: 49%; Non-Hispanic African American: 51%; - Socioeconomic position: parent education ≥college graduate: 49% White, 21% Black; Family income <$50,000: 63% White; 80% Black; - Anthropometry: BMI: White, 17.6 (3.0) kg/m^2^; Black, 18.6 (3.7) kg/m^2^; - Physical activity: NR; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: Ate breakfast all 3 days: 77% White, 57% Black; Excluded from study or analysis: did not self-identify as black or white, non-Hispanic, with racially concordant parents or guardians | Exposure:; Breakfast (0, 1, 2, 3 days) as an average across all time periods (i.e., % of days with any eating between 5–10am on weekdays and 5–11am on weekend); Assessment methods and timing:; - 3d food records (consecutive days including 2 weekdays and 1 weekend day) were used to record all food and drink eaten during breakfast; - Every 1–2y for 9y; Outcomes and assessment methods:; - Annually for 9y; - Height and weight were measured by trained examiners and used to calculate BMI. | [underlined: BMI (kg/m^2^) based on average breakfast intake across 9y], β (SE); Breakfast on 3 days: REF; Breakfast on 2 days: 0.06 (0.04); Breakfast on 1 day: 0.08 (0.05); Breakfast on 0 days: 0.04 (0.07) p=0.38 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, physical activity; - Other: site; site-by-age interaction; race-by-age interaction; Limitations:; - No evidence whether the result was biased due to missing data; - No preregistered data analysis plan; Funding:; NHLBI
Albertson, 2007^2^; PCS, NHLBI Growth and Health Study, U.S.; Analytic N=2,371; Study objective: To describe the pattern of breakfast eating over time (“breakfast history”) and examine its associations with BMI and physical activity; Participant characteristics at baseline: Black and White adolescent females; - Age: 9y; - Female: 100%; - Race and/or ethnicity: Non-Hispanic White: 49%; Non-Hispanic African American: 51%; - Socioeconomic position: parent education ≥college graduate: 49% White, 21% Black; Family income <$50,000: 63% White; 80% Black; - Anthropometry: BMI 18.6 (3.8) kg/m^2^; - Physical activity: physical activity score 452.5 (260.9); - Smoking: NR; - TEI: 1.9 (0.4) kcal/1000; - Habitual diet at baseline: 70.6 (19.2)% days eating breakfast in years 0–10; Excluded from study or analysis: did not self-identify as black or white, non-Hispanic, with racially concordant parents or guardians | Exposure:; Breakfast as an average across all time periods (i.e., % of days with any eating between 5–10am on weekdays and 5–11am on weekend); Assessment methods and timing:; - 3d food records (consecutive days including 2 weekdays and 1 weekend day) were used to record all food and drink eaten during breakfast; - Every 1–2y for 9y; Outcomes and assessment methods:; - Annually for 10y; - Height and weight were measured by trained examiners and used to calculate BMI and BMI-for-age z-scores (BMIz) using CDC age-and-gender specific percentiles. | [underlined: BMIz at 10y follow-up by % of days eating breakfast], β (SE); Multiple imputation: 0.0013 (0.0011), p=NS; Complete case: 0.0015 (0.0011), p=NS; Path analysis (direct): 0.02, p=0.31; [underlined: Change in BMIZ at 10y follow-up by eating breakfast one more day per week], Mean (95% CI), p-value; Baseline BMIz at 50th %tile: 0.02 (−0.01, 0.05), p=0.17; Baseline BMIz at 95th %tile: −0.04 (−0.08, −0.01), p=0.04; Baseline BMIz at 97th %tile: −0.05, (−0.10, −0.01), p=0.01 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, physical activity; - Other: site; eating disorder inventory subscale scores; Limitations:; - No preregistered data analysis plan; Funding:; NHLBI
Barton, 2005^4^; PCS, NHLBI Growth and Health Study, U.S.; Analytic N=2,379; Study objective: To describe changes in breakfast and cereal consumption of girls between ages 9 and 19 years, and to examine the association of breakfast and cereal intake with body mass index and consumption of nutrients; Participant characteristics at baseline: Black and White adolescent females; - Age: 9y; - Female: 100%; - Race and/or ethnicity: Non-Hispanic White: 49%; Non-Hispanic African American: 51%; - Socioeconomic position: parent education ≥college graduate: 49% White, 21% Black; Family income <$50,000: 63% White; 80% Black; - Anthropometry: BMI: White, 17.6 (3.0) kg/m^2^; Black, 18.6 (3.7) kg/m^2^; - Physical activity: NR; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: ~15% days (out of 3) that girls reported no breakfast; Excluded from study or analysis: did not self-identify as black or white, non-Hispanic, with racially concordant parents or guardians | Exposure:; Breakfast as an average across all time periods (i.e., % of days with any eating between 5–10am on weekdays and 5–11am on weekend); also examined as skipped breakfast on all or most days vs consumed breakfast on 3 days; Assessment methods and timing:; - 3d food records (consecutive days including 2 weekdays and 1 weekend day) were used to record all food and drink eaten during breakfast; - Every 1–2y for 9y; Outcomes and assessment methods:; - Annually for 10y; - Height and weight were measured by trained research staff and used to calculate BMI and BMI-for-age z-scores (BMIz). "At risk of overweight" was defined as ≥85th age- and sex-specific BMI percentile based on CDC guidelines. | [underlined: BMIz across 10y by days eating breakfast], Chi-square 4.54, p>0.17; [underlined: BMI (kg/m^2^) across 10y], Mean % of days out of 3 Skipped breakfast on all or most days > Consumed breakfast on 3 days (data not shown); [underlined: Risk of overweight across 10y by days eating breakfast], Chi-square 4.98, p>0.17 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, physical activity; - Other: site; number of parents in household; Limitations:; - No evidence whether the result was biased due to missing data; - No preregistered data analysis plan; Funding:; NHLBI
Bel-Serrat, 2019^5^; PCS, Childhood Obesity Surveillance Initiative, Ireland; Analytic N=1,262; Study objective: To prospectively investigate the predictors of overweight/obesity and of BMI change in schoolchildren; Participant characteristics at baseline: Irish children aged 6–10y; - Age: 7.9 (1.1)y; - Female: 54%; - Race and/or ethnicity: NR; - Socioeconomic position: NR; - Anthropometry: BMI 16.3 kg/m^2^; - Physical activity: 31% attend sports or dance class 0–1 d/wk (30% on 2 d/wk, 24% on 3 d/wk); - Smoking: NR; - TEI: NR; - Habitual diet at baseline: 95% eat breakfast every day; Excluded from study or analysis: missing data on age, sex, weight, or height at one time point | Exposure:; Breakfast (every day vs not every day); Assessment methods and timing:; - Qualitative FFQ completed by parent, with responses of "never/< once a week", "some days (1–3 days)", "most days (4–6 days)", and "every day".; - At baseline; Outcomes and assessment methods:; - At baseline, mean follow-up of 3y; - Weight and height were measured by study personnel and used to calculate BMI-for-age z-scores (BMIz). Underweight/normal weight and overweight/obesity was based on IOTF cut-offs. Prevalence of overweight and obesity was defined as all children who were overweight and obese at follow-up regardless of their baseline weight status. Prevalence of overweight and obesity was defined as all children who were overweight and obese at follow-up regardless of their baseline weight status. Waist circumference was also measured by study personnel and used to calculate waist-for-age z-scores and define abdominal obesity (≥91st%) | [underlined: Change in BMIz], Mean (SD); Breakfast every day: −0.02 (0.50); Not every day: 0.11 (0.55) p=0.124; [underlined: Overweight/obesity at follow-up], OR (95% CI); Prevalence; Breakfast every day: REF; Not every day: 1.69 (0.64, 4.42); Incidence; Breakfast every day: REF; Not every day: 1.71 (0.61, 4.82) | Model adjustments:; - TEI: no; - Key confounders: sex, age, socioeconomic position, anthropometry at baseline, physical activity; - Other: measurement round; time follow-up; school location; birthweight; breastfeeding; fruit intake; vegetable intake fast food intake; savory snack intake; screen time sleep; Limitations:; - Did not account for key confounders: race and/or ethnicity; - Exposure data only assessed at baseline leading to a concern that changes in exposure status occurred over f/u; - Exposure were not well defined and subject to measurement error; - No evidence whether the result was biased due to missing data; - No preregistered data analysis plan; - Did not report results for all measured outcomes; - Water was not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; Health Service Executive of Ireland
Berkey, 2003^6^; PCS, Growing Up Today Study, U.S.; Analytic N=14,586; Study objective: To investigate whether skipping breakfast was prospectively associated with changes in body fatness.; Participant characteristics at baseline: children aged 9–17y, offspring of Nurses’ Health Study II participants; - Age: 9–14y; - Female: 56%; - Race and/or ethnicity: Non-Hispanic White: 95%; Non-Hispanic Black: 1%; Asian: 2%; Other (including Native American): 1%; Hispanic: 2%; - Socioeconomic position: NR; - Anthropometry: Overweight: 23% of boys, 17% of girls; - Physical activity: NR; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: 84% ate breakfast 5–7 d/wk,13% on 3–4 d/wk, 9% on 1–2 d/wk, and 4% never ate breakfast; Excluded from study or analysis: missing data (did not return annual surveys; height more than 3 SD the gender-age-specific mean; BMI <12 kg/m^2^ or >3 SD above or below the gender-age-specific mean; implausible total physical activity (>40hr/wk); physical inactivity >80hr/wk; <500 or >5000 kcal/d | Exposure:; Breakfast frequency (never, 1–2, 2–4, 5–7 days/wk); Assessment methods and timing:; - "How many times each week (including weekdays and weekends) do you eat breakfast?" Response categories were never (or almost never), 1–2 times/wk, 3–4 times/wk, and ≥5 times/wk; - At baseline, 1y and 2y follow-up; Outcomes and assessment methods:; - At baseline, 1y and 2y follow-up; - Height and weight were self-reported and used to calculate BMI | [underlined: Change in BMI (kg/m^2^) over 1y based on breakfast frequency], β (SE); 5–7 days/wk: REF; Boys, Normal Weight; 3–4 days/wk: 0.04 (0.05), p=0.42; 1–2 days/wk: 0.03 (0.06), p=0.62; Never: 0.22 (0.14), p=0.11; Boys, Overweight; 3–4 days/wk: −0.10 (0.11), p=0.40; 1–2 days/wk: −0.03 (0.15), p=0.83; Never: −0.70 (0.23), p=0.01; Girls, Normal Weight; 3–4 days/wk: 0.02 (0.03), p=0.47; 1–2 days/wk: 0.02 (0.04); p=0.62; Never: 0.10 (0.06), p=0.09; Girls, Overweight; 3–4 days/wk: −0.16 (0.11), p=0.16; 1–2 days/wk: −0.31 (0.14), p=0.03; Never: 0.47 (0.15), p=0.01; [underlined: Change in BMI (kg/m^2^) over 3y based on breakfast frequency], β (SE); 5–7 days/wk: REF; Girls, Normal Weight; 1–2 days/wk: 0.072 (0.037); Girls, Overweight; 3–4 days/wk: −0.177 (0.056); 1–2 days/wk: −0.114 (0.067); Boys, Normal Weight; Data NR; Boys, Overweight; 3–4 days/wk: −0.139 (0.071); Never: −0.425 (0.234) | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, anthropometry at baseline, physical activity; - Other: Tanner stage; menarche; inactivity; cereal intake; Limitations:; - Did not account for key confounders: socioeconomic position; - Outcomes were self-reported; - No preregistered data analysis plan; - Water was not accounted for in exposure assessment; Funding:; NIH; CDC; Boston Obesity Nutrition Research Center; USDA
Brophy, 2009^7^; PCS, Millennium Cohort Study, UK; Analytic N=17,561; Study objective: To examine risk factors occurring before age 5 to predict obesity at age 5 by ethnicity; Participant characteristics at baseline: British children; - Age: 3y; - Female: NR; - Race and/or ethnicity: White/European: 86%; African: 4%; Asian: 11%; - Socioeconomic position: ~25% had university level education; income for White/European, Asian, and African participants: <£10,400: 25%, 41%, 53% £10,400-£20,800: 33%, 40%, 26% £20,800+: 42%, 19%, 21%; - Anthropometry: 6% with obesity; - Physical activity: ~77% "enjoy physical activity"; - Smoking: ~10% smoking near child; - TEI: NR; - Habitual diet at baseline: NR; Excluded from study or analysis: non-singletons | Exposure:; Eats breakfast <7 days/wk (yes/no); Assessment methods and timing:; - Parent report; - NR (possibly at 3y); Outcomes and assessment methods:; - At 5y; - Height and weight were measured by study personnel and used to calculate BMI. Obesity was defined by the IOTF cut-offs for age-and-sex-specific BMI | [underlined: Obesity at age 5y], OR (95% CI) Eats breakfast daily: REF; Eats breakfast <7 days/wk: data NR p=NS | Model adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, physical activity; - Other: solid food before 3mo, 1 or less portions of fruit/d, does not eat at regular meal times, watches more than 3hr/d of tv, plays on computer more than 3hr/d, parents plays indoors with child every day, maternal pre-pregnancy weight, smoking near child, birth weight; Limitations:; - Did not account for key confounders: anthropometry at baseline; - Exposure data only assessed at baseline leading to a concern that changes in exposure status occurred over f/u; - Exposure were not well defined and subject to measurement error; - No preregistered data analysis plan; - Water was not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; Welsh Office for Research and Development
Cayres, 2018^8^; PCS, Brazil; Analytic N=86; Study objective: To analyze the longitudinal relationship between breakfast intake and absolute changes in adiposity among adolescents, and the possible role of physical activity to mediate this phenomenon.; Participant characteristics at baseline: adolescents (11–14y); - Age: 11.7y; - Female: 51%; - Race and/or ethnicity: NR; - Socioeconomic position: NR; - Anthropometry: BMI ~21kg/m^2^; - Physical activity: ~4d/wk with >7500 steps; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: 57% skipped breakfast ≥1 days/wk; Excluded from study or analysis: not enrolled in school; known chronic disease; regular medicine use | Exposure:; Breakfast (days/wk); Assessment methods and timing:; - Face-to-face interview using the question: "How many days per week do you usually eat breakfast?" The possible answers were: 0 days, 1–2 days, 3–5 days, and every day of the week. Participants were categorized as "breakfast eaters" or "breakfast skippers" (skipped ≥1 days/wk) based on average of 2 interviews. The scores of both interviews were summed for analysis (ranging from 0–6 days).; - At baseline, 1y follow-up; Outcomes and assessment methods:; - At baseline, 1y follow-up; - Percent body fat and trunk fat were estimated using a densitometry scanner | [underlined: Change in body fatness % over 1y], Pearson correlation (95% CI); −0.272 (−0.458, −0.064); [underlined: Change in trunk fatness % over 1y], Pearson correlation (95% CI); −0.227 (−0.419, −0.016) | Model adjustments:; - TEI: no; - Key confounders: sex, age, anthropometry at baseline; - Other: maturity level, maturity level change; Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position, physical activity; - Exposure was not well defined and subject to measurement error; - Exposure was based on baseline and f/u combined; - Did not provide evidence as to whether the result was unbiased due to missing data; - No preregistered data analysis plan; - Water was not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; State of Sao Paulo Research Support Foundation
Crossman, 2006^9^; PCS, National Longitudinal Study of Adolescent Health, U.S.; Analytic N=6378 (males, n=3144; females, n=3234); Study objective: To examine the effects of the family environment and adolescents’ behaviors while in school (grades 7 through 12) on their weight status 6 years later; Participant characteristics at baseline: adolescents in grades 7–12; - Age: 15.3 (1.6)y; - Female: 51%; - Race and/or ethnicity: White: 59%; Black/African American: 21%; Asian: 7%; Other: 1%; Native American: 10%; Hispanic: 15%; - Socioeconomic position: Parent education level (1 = less than high school, 5 = beyond 4y college degree): 2.7 ; 53% two parent family structure, 24% single parent; - Anthropometry: 15% at risk for overweight, 7% overweight; - Physical activity: 3.7 (2.1) physical activity episodes/wk; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: 19% skipped breakfast; Excluded from study or analysis: missing data; BMI <18.5 kg/m^2^ | Exposure:; Skipping breakfast (yes/no); Assessment methods and timing:; - Single yes/no question; - At baseline; Outcomes and assessment methods:; - At 6y follow-up (when they were 18–26y); - Weight status (overweight and obesity) was based on researcher-measured data and CDC adult guidelines. | [underlined: Overweight/Obesity], OR; Males (n=3144); Does not skip breakfast: REF Skips breakfast: 1.37, p<0.05; Females (n=3234); Does not skip breakfast: REF Skips breakfast: 1.23, p=NS | Model adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, physical activity; - Other: parent weight status, perceptions of family relationships, self-esteem, TV/video games; Limitations:; - Exposure assessment method not validated and only baseline measure used in analysis; - High attrition rate/missing data; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; NICHD
de Winter, 2016^10^; PCS, Tracking Adolescents' Individual Lives Survey (TRAILS), The Netherlands; Analytic N=1,816; Study objective: To examine the prevalence, longitudinal patterns and predictors of individual and multiple health risk behaviors among adolescents.; Participant characteristics at baseline: Dutch adolescents; - Age: 13.6 (0.5)y; - Female: NR; - Race and/or ethnicity: NR; - Socioeconomic position: ~25% low SES; - Anthropometry: 9% overweight or obesity; - Physical activity: 64% physical inactivity; - Smoking: 32% smoking ≥1 cigarettes ever; - TEI: NR; - Habitual diet at baseline: 23% ate breakfast <5 days/wk; Excluded from study or analysis: NR | Exposure:; Breakfast (<5 or ≥5 days/wk); Assessment methods and timing:; - Single yes/no question; - At baseline (T2) and 0.9–4y follow-up (32±7 mo); Outcomes and assessment methods:; - At baseline (T2) and 0.9–4y follow-up (32±7 mo); - BMI was calculated from measured weight and height. Overweight and obesity was defined according to international age- and gender-adjusted BMI criteria. | [underlined: Overweight or obesity by baseline breakfast], OR (95% CI); Breakfast ≥5 days/wk: REF; Breakfast <5 days/wk: 1.41 (0.97, 2.06) | Model adjustments:; - TEI: no; - Key confounders: sex; - Other:; Limitations:; - Did not account for key confounders: age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, physical activity; - Exposure data only assessed at baseline leading to a concern that changes in exposure status occurred over f/u; - Start of follow-up and exposure do not coincide; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; Netherlands Organization for Scientific Research; Dutch Ministry of Justice; European Science Foundation; Biobanking and Biomolecular Resources Research Infrastructure
Drenowatz, 2013^13^; PCS, Baden-Württemberg Study, Germany; Analytic N=1,249; Study objective: To examine the association of physical fitness, sports participation, physical activity, and sedentary behavior as well as dietary patterns and family background with weight gain, independent of absolute body weight, in non-overweight elementary school children.; Participant characteristics at baseline: elementary school children without overweight or obesity; - Age: ~7 (0.6)y; - Female: 49%; - Race and/or ethnicity: 23% migration background (at least one parent born outside Germany or the predominant language at home was not German); - Socioeconomic position: NR; - Anthropometry: 100% non-overweight; - Physical activity: Habitual sports ~230 (200) min/wk; Organized sports ~95 (95) min/qk; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: NR; Excluded from study or analysis: reported chronic disease; with overweight or obesity; lost to follow-up | Exposure:; Regular breakfast (yes/no); Assessment methods and timing:; - Parents were asked how often their children had breakfast prior to going to school; - At baseline; Outcomes and assessment methods:; - At baseline, 1y follow-up; - Height and weight were measured by study personnel and used to calculate BMI percentiles using German reference values. Weight loss was based on a >5 reduction in BMI percentile, and weight gain was based on a >5 increase. Children with a BMI percentile ≤5 were classified as maintaining constant weight. | [underlined: Weight gain (vs weight loss) at 1y follow-up], OR (95% CI); Regular breakfast: REF; No regular breakfast: 0.92 (0.68, 1.25); [underlined: No change in weight (vs. weight loss) at 1y follow-up], OR (95% CI); Regular breakfast: REF; No regular breakfast: 1.05 (0.79, 1.39) | Model adjustments:; - TEI: no; - Key confounders: sex, age, anthropometry at baseline; - Other: none; Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position, physical activity; - Exposure was not defined and subject to measurement error; - Did not provide evidence as to whether the result was unbiased due to missing data; - No preregistered data analysis plan; - Water was not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; Baden-Württemberg Stiftung
Elgar, 2005^15^; PCS, Health Behaviour of School-aged Children Study, UK; Analytic N=355; Study objective: To study the prevalence and stability of overweight and obesity in a cohort of adolescents, and the effects of sedentary behavior and physical activity on changes in body mass.; Participant characteristics at baseline: adolescents 11–14y; - Age: 12.3 (6.3)y; - Female: 55%; - Race and/or ethnicity: NR; - Socioeconomic position: NR; - Anthropometry: 20% with overweight/obesity; - Physical activity: NR; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: NR; Excluded from study or analysis: missing data at baseline or follow-up; in private or special needs schools; incarcerated | Exposure:; Breakfast (number of meals skipped per week); Assessment methods and timing:; - Questionnaire with items related to dieting and meal skipping; - At baseline; Outcomes and assessment methods:; - At baseline, 4y follow-up; - Weight and height were measured by study personnel and used to calculate BMI. | [underlined: BMI (kg/m^2^) at 4y follow up], β (SE); Breakfast meals skipped per week: 0.03 (0.06), p=NS | Model adjustments:; - TEI: no; - Key confounders: sex, age, socioeconomic position, anthropometry at baseline, physical activity; - Other: number of other meals skipped; number of hours per week spent watching television or videos, or playing computer games; Limitations:; - Did not account for key confounders: race and/or ethnicity; - Exposure was only measured at baseline and subject to measurement error; - Did not provide evidence as to whether the result was unbiased due to missing data; - No preregistered data analysis plan; - Water was not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; Welsh Assembly Government
Gingras, 2018^16^; PCS, Project Viva, U.S.; Analytic N=995; Study objective: To examine longitudinal associations of dietary behaviors throughout childhood with adiposity and estimated insulin resistance (HOMA-IR) in adolescence; Participant characteristics at baseline: children from a pre-birth cohort; - Age: ~4y; - Female: 51%; - Race and/or ethnicity: White: 65%; Black: 3%; Asian: 16%; Other: 12%; Hispanic: 5%; - Socioeconomic position: 71% maternal education ≥college degree; 64% with annual household income >$70k; - Anthropometry: BMIz 0.37 at age 4y; - Physical activity: NR; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: 86% ate breakfast daily at 4y; Excluded from study or analysis: missing data on covariates, dietary behaviors, or outcomes | Exposure:; Eating breakfast (always/daily vs ≤6x/wk); Assessment methods and timing:; - Mothers reported their children's average frequency of eating breakfast over the previous month from ages 4–8y, and children reported this information from ages 9–10y.; - Annually from age 4–10y; Outcomes and assessment methods:; - At age 13.2 (0.9)y; - Weight and height were measured by study personnel and used to calculate age- and sex-specific BMI z-scores (BMIz). Waist circumference (WC) was measured. Whole-body fat percentage was measured using bio-impedance. Some participants (n=721) completed DEXA at an in-person visit, which was used to derive whole-body fat percentage, trunk fat mass, and trunk to peripheral fat mass ratio. | [underlined: BMIz at 13y based on eating breakfast daily from 4–10y], β (95% CI); Boys: −0.13 (−0.24, −0.02); Girls: −0.13 (−0.23, −0.02); [underlined: WC (cm) at 13y based on eating breakfast daily from 4–10y], β (95% CI); Boys: −0.60 (−1.87, 0.68); Girls: −1.59 (−2.67, −0.51); [underlined: Whole-body fat % at 13y based on eating breakfast daily from 4–10y], β (95% CI); Bioimpedance; Boys: −0.94 (−1.92, 0.05); Girls: −1.47 (−2.39, −0.54); DEXA; Boys: −1.43 (−2.42, −0.45); Girls: −1.47 (−2.25, −0.68); [underlined: Trunk fat mass (kg) at 13y based on eating breakfast daily from 4–10y], β (95% CI); Boys: −0.40 (−0.88, 0.08); Girls: −0.92 (−1.33, −0.51); [underlined: Trunk:peripheral fat at 13y based on eating breakfast daily from 4–10y], β (95% CI); Boys: −0.02 (−0.03, −0.01); Girls: −0.05 (−0.06, −0.03) | Model adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position; - Other: maternal parity; pre-pregnancy BMI; Limitations:; - Did not account for key confounders: anthropometry at baseline, physical activity; - Exposure was subject to measurement error; - No preregistered data analysis plan; - Water was not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; NIH; Department of Population Medicine of Harvard Pilgrim Health Care Institute and Harvard Medical School
Goff, 2019^17^; PCS, Determinants of Adolescent Social wellbeing and Health (DASH) cohort, UK; Analytic N=665; Study objective: To describe longitudinal patterns of dietary intake and investigate their impact on cardiometabolic risk in young adulthood; Participant characteristics at baseline: students from secondary schools; - Age: 11–13y; - Female: 51%; - Race and/or ethnicity: White British: 16%; Black African: 20%, Black Caribbean: 15%; Bangladeshi/Pakistani: 17%, Indian: 15%; Other (mainly mixed ethnicity): 17%; - Socioeconomic position: NR; 47% with university degree at follow-up; - Anthropometry: NR; 39% with overweight or obesity at follow-up; - Physical activity: NR; ~738 min/d sedentary time at follow-up; - Smoking: NR; 24% current at follow-up; - TEI: NR; 2192 (2097–2288) kcal/d at follow-up; - Habitual diet at baseline: NR; 56% skipped breakfast at follow-up; Excluded from study or analysis: NR | Exposure:; Skipping breakfast <5 days/wk (yes vs no); Assessment methods and timing:; - "Before going to school, how often do you have breakfast at home or at a school breakfast club? (every day, 3–4 days a week, 1–2 days a week, never or hardly ever). Responses were recoded into skipping breakfast, which was defined as not consuming breakfast every day.; - At baseline (11–13y), 10y follow-up (21–23y); Outcomes and assessment methods:; - At 21–23y; - Weight and height were measured by study personnel and used to calculate BMI. Waist circumference was measured by study personnel and used to calculate waist:height ratio. | [underlined: Waist:Height ratio at 21–23y based on skipping breakfast at 11–13y], β (95% CI); Not skipping breakfast: REF; Skipping breakfast: 0.02 (0.01, 0.03), p<0.001; [underlined: BMI (kg/m^2^) at 21–23y based on skipping breakfast at 11–13y], β (95% CI); Not skipping breakfast: REF; Skipping breakfast: 1.41 (0.57, 2.26), p<0.001 | Model adjustments:; - TEI: yes; - Key confounders: sex, race and/or ethnicity, socioeconomic position, physical activity; - Other: saturated fat intake at follow-up; smoking at follow-up; Limitations:; - Did not account for key confounders: age, anthropometry at baseline; - Exposure was subject to measurement error; - Did not provide evidence as to whether the result was unbiased due to missing data; - No preregistered data analysis plan; - Water was not accounted for in exposure assessment; Funding:; Medical Research Council, Chief Scientist Office, North Central London Research Consortium; Primary Care Research Network
Haerens, 2010^20^; PCS, Longitudinal Eating and Activity study, Belgium; Analytic N=585; Study objective: To explore the relationship between several physical activity and dietary behaviours and BMI Z-score and to investigate the relationship between changes in these variables and in the BMI Z-score over a 4-year period from childhood to adolescence.; Participant characteristics at baseline: fifth grade children; - Age: 10 (0.4) y; - Female: 48%; - Race and/or ethnicity: Belgian nationality: 98%; - Socioeconomic position: NR; - Anthropometry: BMI 16.5 (2.5) kg/m^2^; - Physical activity: NR; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: NR; Excluded from study or analysis: lost to follow-up | Exposure:; Breakfast frequency (days/wk); Assessment methods and timing:; - Children reported how many days in a week and in a weekend they had breakfast. Response categories were ‘never,’ ‘1 d’, ‘2 d (so far the categories for weekends)’, ‘3 d’, ‘4 d’ and ‘5 d’. A composite measure was created that added up the number of days children had breakfast.; - At baseline, annually for 4y; Outcomes and assessment methods:; - At baseline, annually for 4y; - Weight and height were self-reported and used to calculated BMI z-scores on the bases of Flemish reference data using the least mean square method | [underlined: BMIz across 4y follow-up], β (SE); Breakfast intake: −0.04 (0.01), p<0.01; Change in breakfast intake: −0.03 (0.02), p=NS | Model adjustments:; - TEI: no; - Key confounders: sex, age, socioeconomic position, anthropometry at baseline, physical activity; - Other: time; frequency of fruit, vegetable, soft drink, and sweets consumption; Limitations:; - Did not account for key confounders: race and/or ethnicity; - Exposure was only measured at baseline and subject to measurement error; Did not provide evidence as to whether the result was unbiased due to missing data; Outcome data were self-reported; No preregistered data analysis plan; Water was not accounted for in exposure assessment; Did not adjust for TEI; Funding:; Ghent University Research Foundation; Flemish Research Foundation; EU-funded HOPE project
Haines, 2007^21^; PCS, Project EAT, U.S.; Analytic N=2,516; Study objective: To examine a breadth of personal, behavioral, and socio-environmental factors as potential risk and protective factors of overweight among male and female adolescents.; Participant characteristics at baseline: adolescents in middle and high school; - Age: 12.8 (0.8)y −15.8 (0.8)y; - Female: 55%; - Race and/or ethnicity: White: 48%; Black: 19%; Asian: 20%; Native American: 4%; Mixed race or other: 4%; Hispanic: 6%; - Socioeconomic position: 37% low or middle SES; - Anthropometry: 26% overweight or obesity; - Physical activity: MVPA: Girls, 5.8 (4.7) hrs/wk; Boys, 7.4 (4.7) hrs/wk; - Smoking: NR; - TEI: Girls, 1994 (1047) kcal/d; Boys, 2249 (1216) kcal/d; - Habitual diet at baseline: Breakfast 3.5 (2.6) times/wk; Excluded from study or analysis: lost to follow-up | Exposure:; Breakfast (times/wk); Assessment methods and timing:; - “During the past week, how many days did you eat breakfast?” The responses (never, 1 or 2 days, 3 or 4 days, 5 or 6 days, everyday) were coded using the midpoints of each category (0, 1.5, 3.5, 5.5, and 7 days per week); - At baseline, 5y follow-up; Outcomes and assessment methods:; - At baseline, 5y follow-up; - Weight and height were self-reported and used to calculate BMI. BMI >85th percentile for age and gender was defined as “overweight.” | [underlined: Overweight at 5y follow up], OR (95% CI); Females; Baseline intake: 0.89 (0.83, 0.97), p<0.05; Change in intake: Data NR, p<0.05; Males; Baseline intake: 0.89 (0.82, 0.97), p<0.05; Change in intake: Data NR, p=NS; [underlined: Incidence of overweight], OR (95% CI); Females; Baseline intake: 0.84 (0.74, 0.96), p<0.05; Change in intake: Data NR, p<0.05; Males; Baseline intake: 0.84 (0.74, 0.96), p<0.05; Change in intake: Data NR, p<0.05 | Model adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline; - Other: cohort; Limitations:; - Did not account for key confounders: physical activity; - Did not provide evidence as to whether the result was unbiased due to missing data; - Outcome data were self-reported; - No preregistered data analysis plan; - Water was not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; Maternal and Child Health Bureau (HHS)
Hassan, 2019^22^; PCS, Adolescent Nutritional Assessment Longitudinal Study (ELANA), Brazil; Analytic N=809; Study objective: To investigate the relationship between breakfast and family breakfast frequency and adiposity trajectory in adolescence.; Participant characteristics at baseline: middle school students aged 10–16y; - Age: 11.8y; - Female: 61%; - Race and/or ethnicity: White: 46%; - Socioeconomic position: 63% from private school; - Anthropometry: 24% with overweight, 18% with obesity; - Physical activity: 23% with <2 hr/d of screen time; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: 74% had breakfast ≥5 days/wk, 16% had breakfast 1–4 days/wk, 10% skipped breakfast; Excluded from study or analysis: lost to follow-up; pregnant or lactating; physical or mental disabilities | Exposure:; Breakfast: no consumption (never/almost never), intermediate (1–4 days/wk), regular (≥5 days/wk); Also categorized as: persistent regular consumption (≥5 days/wk at both baseline and follow-up), regular consumption at baseline, regular consumption at follow-up, and persistent irregular consumption (<5 days/wk at both baseline and follow-up); Assessment methods and timing:; - “How often do you eat the following meals?” Five response options for both items were given: “never or almost never,” “1 or 2 times a week,” “3 or 4 times a week,” “5 or 6 times a week,” and “daily.” Never or almost never was considered no consumption, 1–4 times a week was considered intermediate consumption, and ≥5 times a week was considered regular consumption.; - At baseline, 3y follow-up; Outcomes and assessment methods:; - At baseline, 3y follow-up; - Weight and height were measured by study personnel and used to calculate BMI-for-age z scores based on WHO. Body fat % (BF%) was measured using bioelectrical impedance. | [underlined: Change in BF% over 3y based on baseline breakfast intake], Mean (SD); Baseline to 1y, 2y, and 3y follow-up; Boys; No consumption: −2.4 (3.8), −3.8 (4.4), −5.3 (4.0); Intermediate: −2.1 (3.1), −3.9 (5.3), −4.3 (5.8); Regular: −1.2 (4.3), −2.8 (5.2), −3.6 (6.0) p=NS; Girls; No consumption: 0.5 (3.3), 1.4 (5.0), 2.6 (4.8); Intermediate: 0.2 (3.8), 0.7 (5.0), 2.1 (5.4); Regular: 0.2 (4.4), 2.4 (4.5), 4.2 (4.4); Smaller increase in intermediate breakfast consumers vs. regular consumers (p<0.05); [underlined: Change in BF% over 3y based on change in breakfast over 3y]; Boys: NS; Girls: Smaller increase in persistently intermediate breakfast consumers vs. persistently regular consumers (p<0.05); [underlined: Change in BMI (kg/m^2^) over 3y based on baseline breakfast intake], Mean (SD); Baseline to 1y, 2y, and 3y follow-up; Boys; No consumption: 0.8 (1.4), 1.5 (1.6), 2.2 (1.9); Intermediate: 0.3 (1.2), 0.8 (2.1), 1.8 (2.5); Regular: 0.7 (1.1), 1.3 (1.5), 1.7 (1.7) p=NS; Girls; No consumption: 0.8 (1.3), 1.6 (1.9), 2.1 (2.0); Intermediate: 1.1 (1.3), 1.3 (2.0), 1.6 (2.6); Regular: 0.7 (1.4), 1.6 (1.9), 2.1 (2.0) p=NS; [underlined: Change in BMI (kg/m^2^) over 3y based on change in breakfast over 3y]; Data NR, p=NS | Model adjustments:; - TEI: no; - Key confounders: sex, age, socioeconomic position, anthropometry at baseline, physical activity; - Other: Screen time; dieting; sexual maturation; family breakfast frequency; Limitations:; - Did not account for key confounders: race and/or ethnicity; - Exposure was subject to measurement error; - No preregistered data analysis plan; - Water was not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; National Council for Scientific and Technological Development; Research Support Foundation of the State of Rio de Janeiro; Coordination for the Improvement of Higher Education Personnel
Ikeda, 2019^23^; PCS, Longitudinal Survey of Newborns in the 21st Century, Japan; Analytic N=15,427; Study objective: To assess longitudinal changes in the first incidence of overweight and obesity and associated factors from preschool to primary school age in Japan.; Participant characteristics at baseline: preschool-aged children; - Age: 42–66 mo; - Female: 48%; - Race and/or ethnicity: NR, likely majority Asian; - Socioeconomic position: 17% maternal education university or higher; - Anthropometry: 7% overweight or obesity; - Physical activity: NR; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: 78% no breakfast skipping; Excluded from study or analysis: missing data or lost to follow-up | Exposure:; Skipping breakfast (yes/no); Assessment methods and timing:; - Survey on behavioral factors, including skipping breakfast. Skipping breakfast was asked and coded in the 5th, 7th, and 8th surveys as self-reporting skipping breakfast every day or occasionally and in the 9th −12th surveys as self-reporting usually having no breakfast.; - At 5th (54mo) and 7th −12th surveys (6–12y); Outcomes and assessment methods:; - Annually for 12y; - Height and weight were self-reported and using to calculate BMI. Overweight and obesity were defined according to IOTF reference values specific for sex and age in months that corresponded to BMI of 25 and 30 kg/m^2^, respectively, at age 18y | [underlined: Overweight/obesity at 7–12y based on breakfast skipping at 54mo], OR (95% CI); Not skipping: REF Skipping: 1.52 (1.27, 1.83) | Model adjustments:; - TEI: no; - Key confounders: sex, age, socioeconomic position, anthropometry at baseline; - Other: birthweight; gestational length; regions and municipal types of residence; living without siblings or with grandparents in the same household as markers of family structure; weekday bedtime hours; time spent watching television per weekday; mode of travel to school; Limitations:; - Did not account for key confounders: race and/or ethnicity, physical activity; - Exposure was not well defined and subject to measurement error; - Exposure data only assessed at baseline; - Did not provide evidence as to whether the result was unbiased due to missing data; - Outcomes were self-reported, No preregistered data analysis plan; - Water was not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; Ministry of Health, Labor and Welfare of Japan
Jeans, 2022^24^; PCS, Secondary analysis of TX Sprouts RCT, U.S.; Analytic N=1,417; Study objective: To examine the intervention effect on breakfast consumption and how changes in breakfast consumption impact cardiometabolic risk in predominately low-income, multi-ethnic children; Participant characteristics at baseline: low-income Hispanic children 7–12y; - Age: 9.3 (0.9)y; - Female: 47%; - Race and/or ethnicity: Non-Hispanic White: 29%; Non-Hispanic Black: 8%; Other: 5%; Hispanic: 58%; - Socioeconomic position: 63% of children participated in the free and reduced-price school meal program; - Anthropometry: 44% overweight or obesity; - Physical activity: NR; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: 63% breakfast maintainers, 16% breakfast decreasers, 21% breakfast increasers; Excluded from study or analysis: missing data | Exposure:; Breakfast consumption (days/wk; maintainers vs. breakfast decreasers vs. breakfast increasers); - Breakfast maintainers: those who had minimal change in breakfast consumption (change of −1 to 1 breakfast occasions); - Breakfast decreasers: those who had negative change in breakfast consumption (change of ≤-2); - Breakfast increasers: those who had positive change in breakfast consumption (change of >2); Assessment methods and timing:; - Validated survey questions: "How many school days each week do you typically eat breakfast? ( None, 1 school day, 2 school days, 3 school days, 4 school days, 5 school days). How many weekend days each week do you typically eat breakfast? (None, 1 weekend day, 2 weekend days)"; - Beginning and end of school year (~8–9mo apart); Outcomes and assessment methods:; - Beginning and end of school year (~8–9mo apart); - Height, weight, and waist circumference measured by study personnel. BMI was calculated and BMI percentiles were based on CDC age- and sex-specific values. Body fat percentage (BF%) was measured using bioelectrical impedance. | [underlined: Change in WC (cm)]; By 1-day increase in breakfast consumption, β (95% CI); 0.01 (−0.09, 0.11), p=0.88; By categorical changes in breakfast consumption, Mean (SD); Maintainers: 1.4 (3.7); Decreasers: 1.5 (4.2); Increasers: 1.5 (3.4) p=0.50; [underlined: Change in BF%]; By 1-day increase in breakfast consumption, β (95% CI); −0.02 (−0.09, 0.06), p=0.67; By categorical changes in breakfast consumption, Mean (SD); Maintainers: −0.5 (2.6); Decreasers: −0.3 (3.0); Increasers: −0.5 (3.0) p=0.64; [underlined: Change in BMI percentile]; By 1-day increase in breakfast consumption, β (95% CI); −0.09 (−0.33, 0.15), p=0.34; By categorical changes in breakfast consumption, Mean (SD); Breakfast Maintainers: 0.8 (9.3); Breakfast Decreasers: 0.4 (9.1); Breakfast Increasers: 1.1 (7.9) p=0.88 | Model adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, physical activity; - Other: school site; breakfast location; Limitations:; - Did not provide evidence as to whether the result was unbiased due to missing data; - No preregistered data analysis plan; - Water was not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; NHLBI
Kelly, 2016^25^; PCS, Millennium Cohort Study, UK; Analytic N=16,936; Study objective: To identify BMI developmental trajectories across the first decade of life, examine early life predictors of trajectory membership, and investigate whether being on a particular BMI trajectory is associated with markers of psychosocial well-being.; Participant characteristics at baseline: birth cohort from ages 3, 5, 7, and 11y; - Age: 5y; - Female: 49%; - Race and/or ethnicity: White: 87%; Black African: 2%; Black Caribbean: 2%; Indian: 2%; Pakistani: 3%; Bangladeshi: 1%; Other: 2%; - Socioeconomic position: 29% maternal degree, professional diploma, or higher; 31% with higher managerial, administrative, professional occupational class; - Anthropometry: BMI 16.4 (1.9) kg/m^2^; 84% non-overweight BMI; - Physical activity: 45% participate in sports <1 time/wk; - Smoking: 23% smoked during pregnancy; - TEI: NR; - Habitual diet at baseline: 7.5% skips breakfast; Excluded from study or analysis: lost to follow-up; missing outcome data; outlier BMI values | Exposure:; Skips breakfast (yes/no); Assessment methods and timing:; - "How many days a week does he/she usually eat breakfast?" (none to 7); - 5y; Outcomes and assessment methods:; - At 3y, 5y, 7y, and 11y; - Height and weight were measured by study personnel and used to calculate BMI. Trajectories of BMI were identified using latent class growth analysis and a 4-trajectory model was chosen for analysis based on IOTF age-specific cut-off points for overweight and obesity:; - Stable non-overweight from 3–11y; - Decreasing (obesity at 3y and subsequent decreases through 11y); - Moderate increasing (non-overweight at 3y with subsequent increases into overweight range through 11y); - High increasing BMI trajectory (obesity at 3y and subsequent increases through 11y) | [underlined: BMI trajectory across ages 3–11y based on skipping breakfast at age 5y], OR (95% CI); Stable: REF; Decreasing: 2.01 (1.03, 3.92), p<0.05; Moderate increasing: 1.66 (1.37, 2.02), p<0.001; High increasing: 1.76 (1.21, 2.56), p<0.01 | Model adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline; - Other: none; Limitations:; - Did not account for key confounders: physical activity; - Exposure was not well defined and subject to measurement error; - Unclear when exposure was measured relative to outcome measurements; - Did not provide evidence as to whether the result was unbiased due to missing data; - No preregistered data analysis plan; - Water was not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; Economic and Social Research Council
Kesztyus, 2016^27^; PCS, Secondary analyses of Baden-Württemberg Study cluster-RCT, Germany; Analytic N=1,545; Study objective: To investigate correlates of changes in waist-to-height ratio in primary school children in order to identify modifiable factors usable for prevention.; Participant characteristics at baseline: 1st and 2nd graders; - Age: 7.1 (0.6)y; - Female: 49%; - Race and/or ethnicity: 31% with migration background (≥1 parent born abroad or mainly speaking non-German language); - Socioeconomic position: 32% tertiary family educational level; 13% household income <1750 Euros; 10% single parent; - Anthropometry: BMI 15.98 (2.14) kg/m^2^; 10% with overweight, 4% with obesity; - Physical activity: 27% physically active ≥4 d/wk for ≥60 min/d; - Smoking: 37% smoking mother or father; - TEI: NR; - Habitual diet at baseline: 13% skipping breakfast; Excluded from study or analysis: lost to follow-up; missing data | Exposure:; Breakfast skipping (yes/no); Assessment methods and timing:; - On a 4-point Likert scale, parents stated how often their children ate breakfast before going to school. The answers also were dichotomized: “Never and rarely” versus “often and always”.; - At baseline; Outcomes and assessment methods:; - At baseline, 1y follow-up; - Waist circumference was measured by study personnel and used to calculate waist-to-height ratio. | [underlined: Change in waist to height ratio over 1y by skipping breakfast at baseline], β±SE; 0.39 (0.19), p<0.05; Adjusting for school-level clustering: 0.36±0.19, p<0.10 | Model adjustments:; - TEI: no; - Key confounders: age, socioeconomic position, anthropometry at baseline, physical activity; - Other: migration background; parental smoking; screen time; breastfeeding; parental overweight and abdominal obesity; school cluster; soft drink intake; parental health awareness; Limitations:; - Did not account for key confounders: sex, race and/or ethnicity; - Exposure was not well defined and subject to measurement error; - Did not provide evidence as to whether the result was unbiased due to missing data; - No preregistered data analysis plan; - Water was not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; Baden-Württemberg Stiftung
Kesztyus, 2017^26^; PCS, Secondary analyses of Baden-Württemberg Study cluster-RCT, Germany; Analytic N=1,733; Study objective: To evaluate the cost-effectiveness of the state-wide implementation of the health promotion program "Join the Healthy Boat" in primary schools in Germany.; Participant characteristics at baseline: 1st and 2nd graders; - Age: 7.1 (0.6)y; - Female: 49%; - Race and/or ethnicity: 31% with migration background (≥1 parent born abroad or mainly speaking non-German language); - Socioeconomic position: 32% tertiary family educational level; 13% household income <1750 Euros; 10% single parent; - Anthropometry: BMI 15.98 (2.14) kg/m^2^; 10% with overweight, 4% with obesity; - Physical activity: 27% physically active ≥4 d/wk for ≥60 min/d; - Smoking: 20% smoking mother; 29% smoking father; - TEI: NR; - Habitual diet at baseline: 13% skipping breakfast; Excluded from study or analysis: lost to follow-up; missing data | Exposure:; Breakfast skipping (yes/no); Assessment methods and timing:; - On a 4-point Likert scale, parents stated how often their children ate breakfast before going to school. The answers also were dichotomized: “Never and rarely” versus “often and always”.; - At baseline; Outcomes and assessment methods:; - At baseline, 1y follow-up; - Waist circumference was measured by study personnel and used to calculate waist-to-height ratio. Abdominal obesity was defined as waist-to-height ratio ≥0.5 | [underlined: Abdominal obesity at 1y follow-up by skipping breakfast at baseline], OR (95% CI); Complete breakfast data (n=1538): 3.68 (1.85, 7.33) Missing breakfast data imputed (n=1733): 3.03 (1.59, 5.79) | Model adjustments:; - TEI: no; - Key confounders: sex, age, anthropometry at baseline; - Other: intervention group; Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position, physical activity; - Exposure was not well defined and subject to measurement error; - Did not provide evidence as to whether the result was unbiased due to missing data; - No preregistered data analysis plan; - Water was not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; Baden-Württemberg Stiftung
Kunaratnam, 2022^30^; PCS, Secondary analysis of Healthy Beginnings Trial, Australia; Analytic N=327; Study objective: To examine changes in children's lifestyle behaviors from ages 2–5y to determine if maternal sociodemographic factors and BMI predict child obesity at 3.5y and 5y; Participant characteristics at baseline: preschool-aged children; - Age: 2y; - Female: 50%; - Race and/or ethnicity: NR; - Socioeconomic position: High school: 13%, Technical or further education: 56%, University: 31%; <$40k AUD: 21%, $40–80k, 31%, >$80k: 48%; - Anthropometry: 14% overweight or obesity; - Physical activity: 2.22 (1.21) hr/d outdoor playtime; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: Breakfast, 6.87 (0.81) d/wk; Excluded from study or analysis: lost to follow-up; missing data | Exposure:; Breakfast (days/wk); Assessment methods and timing:; - FFQ, frequency per week of eating breakfast; - At baseline, 1.5y and 3y follow-up; Outcomes and assessment methods:; - At baseline, 1.5y and 3y follow-up; - Height and weight were measured by study personnel and used to calculate BMI. BMI was used to categorize participants as having overweight or obesity, or not, based on IOTF criteria | [underlined: Overweight/obesity], β (95% CI) univariate analysis At 3.5y by breakfast at 2y: p=NS (data not reported) At 5y by breakfast at 3.5y: 0.88 (0.72, 1.08), p=0.22 | Model adjustments:; - TEI: no; - Key confounders: none; - Other: none; Limitations:; - Did not account for key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, physical activity; - Exposure was subject to measurement error; - Did not provide evidence as to whether the result was unbiased due to missing data; - No preregistered data analysis plan; - Water was not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; Australian National Health and Medical Research Council
Kupers, 2014^31^; PCS, GECKO Drenthe cohort, The Netherlands; Analytic N=1,366; Study objective: To examine the association between breakfast skipping and objectively measured overweight at the age of 2 and 5 years; Participant characteristics at baseline: birth cohort; - Age: 2y; - Female: 50%; - Race and/or ethnicity: NR; - Socioeconomic position: Low/middle educational level, mother: 63%; - Anthropometry: 8% overweight; - Physical activity: NR; - Smoking: NR; - TEI:; - Habitual diet at baseline: 3% skipped breakfast; Excluded from study or analysis: lost to follow-up; missing data | Exposure:; Skipping breakfast (not skipping breakfast at 2y and 5y vs continued skipping breakfast at 2y and 5y); Assessment methods and timing:; - ‘How often does your child eat breakfast weekly?’ with answer categories ranging from 1 to 7 days per week. The answer categories were combined as either ‘eating breakfast daily’ (7 times per week) or ‘not eating breakfast daily’ (<7 times per week). For longitudinal analysis, the scores for skipping breakfast at 2 and 5 years were combined. The categories for this analysis were (1) not skipping breakfast at 2 and 5 years, (2) not skipping breakfast at 2 but skipping breakfast at 5 years, (3) skipping breakfast at 2 but not at 5 years and (4) continued skipping breakfast at 2 and 5 years.; - At baseline, 3y follow-up; Outcomes and assessment methods:; - At baseline, 3y follow-up; - Anthropometric measurements recorded by trained nurses. Body mass index (BMI) z-scores were based on age- and gender-specific Dutch reference growth charts of 1997 using Growth Analyser. Overweight was dichotomized on the basis of the z-scores. | [underlined: Overweight at 5y], OR (95% CI); Not skipping breakfast at 2y and 5y: REF; Skipping breakfast at 2y and 5y: 0.72 (0.15, 3.49) | Model adjustments:; - TEI: no; - Key confounders: sex, age, socioeconomic position; - Other: birth weight; origin (Dutch vs non-Dutch); maternal and paternal BMI; single-parent family; Limitations:; - Did not account for key confounders: race and/or ethnicity, anthropometry at baseline, physical activity; - Exposure was subject to measurement error; - Described exposure groups in the methods that were not reported in outcomes; - Did not provide evidence as to whether the result was unbiased due to missing data; - No preregistered data analysis plan; - Water was not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; NR
Larson, 2018^33^; PCS, Project EAT, U.S.; Analytic N=1120; Study objective: To identify personal, behavioral, and environmental factors that predicted healthy weight maintenance during the transition from adolescence to adulthood and as individuals progressed from the third to fourth decade of life.; Participant characteristics at baseline: adolescents; - Age: 14.9 (1.7)y at Time 1; - Female: 45%; - Race and/or ethnicity: White: 50%; African American: 17%; Asian: 20%; Native American: 3%, Mixed or other: 5%; Hispanic: 5%; - Socioeconomic position: NR; - Anthropometry: NR; - Physical activity: NR; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: NR; Excluded from study or analysis: those without height and weight data at ≥1 timepoint; women who were pregnant when they reported their adult weight at Time 3 or 4; adults with BMI <18.5 kg/m^2^ at Time 4 | Exposure:; Breakfast (times/wk); Assessment methods and timing:; - "During the past week, how many days did you eat breakfast?" Five responses ranging from never (coded 0) to every day (coded 7).; - At baseline (Time 1, 1998–1999), 10y follow-up, (Time 3, 2008–2009), and 17y follow-up (Time 4, 2015–2016); Outcomes and assessment methods:; - At baseline (Time 1, 1998–1999), 10y follow-up, (Time 3, 2008–2009), and ~15y follow-up (Time 4, 2015–2016); - Weight and height were self-reported and used to calculate BMI. Healthy weight status (i.e., non-overweight BMI) was defined using screening guidelines: BMI <85%tile for sex and age at Time 1 and BMI <25 kg/m^2^ at Time 3 and Time 4.; - Healthy weight maintenance from adolescence to young adulthood was defined by a non-overweight BMI at Time 1, Time 3, and Time 4. | [underlined: Healthy weight maintenance at Time 4], OR (95% CI); By breakfast frequency at Time 1; Women: 1.08 (0.88, 1.33); Men: 1.06 (0.87, 1.29); By change in breakfast frequency from Time 1 to Time 4; Women: 1.06 (0.8, 1.38); Men: 1.35 (1.03, 1.76) | Model adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline; - Other: none; Limitations:; - Did not account for key confounders: physical activity; - Outcomes were self-reported; No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; NHLBI
Laska, 2012^34^; PCS, IDEA and ECHO, U.S.; Analytic N=693; Study objective: To examine the extent to which changes in adolescent sugar-sweetened beverage, diet soda, breakfast, and fast-food consumption were associated with changes in BMI and percent body fat.; Participant characteristics at baseline: 6th-11th grade students from 2 cohorts; - Age: 14.6 (1.8)y; - Female: 51%; - Race and/or ethnicity: White: ~85%; - Socioeconomic position: ~75% parent college graduate; ~11% eligible for free or reduced-price school lunch; - Anthropometry: BMI 22 (5) kg/m^2^; - Physical activity: ~300 min/d; - Smoking: NR; - TEI: ~1900 kcal/d; - Habitual diet at baseline: Breakfast ~1 days/wk; Excluded from study or analysis: lost to follow-up, missing data | Exposure:; Breakfast (days/wk); Assessment methods and timing:; - 24hr recall; breakfast consumption was defined as the % of recall days on which participants reported a meal called breakfast that contained ≥50 kcal.; - At baseline, 2y follow-up; Outcomes and assessment methods:; - At baseline, 2y follow-up; - Height and weight were measured by study personnel and used to calculate BMI. Percent body fat was measured using bioelectrical impedance. | [underlined: Change in body fat % over 2y by change in breakfast (days/wk)], β (SE); Males; TEI adjusted: −1.80 (1.23), p=0.14; TEI not adjusted: −1.47 (1.27), p=0.25; Females; TEI adjusted: −0.38 (0.86), p=0.66; TEI not adjusted: −0.18 (0.86), p=0.83; [underlined: Change in BMI (kg/m^2^) over 2y by change in breakfast intake (days/wk)], β (SE); Males; TEI adjusted: −0.21 (0.48), p=0.65; TEI not adjusted: −0.19 (0.48), p=0.69; Females; TEI adjusted: −0.31 (0.45), p=0.49; TEI not adjusted: −0.26 (0.46), p=0.57 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, physical activity; - Other: puberty; study; Limitations:; - Exposure was subject to measurement error; - Did not provide evidence as to whether the result was unbiased due to missing data; - No preregistered data analysis plan; - Water was not accounted for in exposure assessment; Funding:; NCI; NHLBI
Lee, 2009^36^; PCS, National Longitudinal Study of Adolescent Health, U.S.; Analytic N=9,730; Study objective: To examine the relationship between childhood poverty/welfare receipt and obesity onset and continuity from adolescence into young adulthood; Participant characteristics at baseline: adolescents in grades 7 to 12; - Age: 15y; - Female: 51%; - Race and/or ethnicity: White: 69%; Black: 15%; Asian: 3%; Other: 1%; Hispanic: 11%; - Socioeconomic position: 64% parent education less than high school; 29% welfare or poverty status (<$16,000/y); - Anthropometry: 14% obesity; - Physical activity: ~6.5 bouts of physical activity/wk; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: Breakfast skipping 6–7x/wk: Females: 13%; Males: 9%; Excluded from study or analysis: lost to follow-up; missing data; seriously disabled respondents; pregnant females | Exposure:; Skips breakfast (yes/no); Assessment methods and timing:; - Questionnaire from in-home interview; variables indicated whether the respondent reported usually eating nothing for breakfast at WI and eating breakfast 0–2 days in a week at WII.; - At WI (1995) and WII (1996); Outcomes and assessment methods:; - At WII (1996) and WIII (2001–02); - Height and weight were measured and used to calculate BMI. Obesity was defined as BMI ≥30 kg/m^2^ based on IOTF age- and sex-specific cut-offs, which was used to create 4 groupings: obesity incidence(no obesity at WII, obesity at WIII), obesity persistence (obesity at WII and WIII), reduction in obesity (obesity in WII, no obesity in WIII), stay in non-obesity (no obesity at both WII and WIII) | [underlined: Obesity incidence over ~6y by skipping breakfast], B* (SE); REF: Stay non-obesity Females: 0.20 (0.15), p=NS; Males: 0.63 (0.18), p=0.01; [underlined: Obesity persistence over ~6y by skipping breakfast], B* (SE); REF: Reduction in obesity Females: 0.60 (0.20), p=0.01; Males: 0.87 (0.20), p=0.001; * Estimated multinomial regression coefficient | Model adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, physical activity; - Other: inadequate sleep; eating dinner with parents; no curfew; parental obesity; Limitations:; - Exposure was not well defined and subject to measurement error; - No preregistered data analysis plan; - Water was not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; NIH
Lee, 2018^35^; PCS, South Korea; Analytic N=93; Study objective: To investigate behavioral factors that contribute to the development of obesity among overweight children; Participant characteristics at baseline: elementary and middle school students aged 9–13y; - Age: ~10–11 (1.4)y; - Female: 24%; - Race and/or ethnicity: NR, likely majority Asian; - Socioeconomic position: NR; - Anthropometry: BMI ~23 (1) kg/m^2^; ~23 (3)% body fat; - Physical activity: Physical fitness score: ~36; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: 16% eat breakfast ≤2x/wk, 18% 3–5x/wk, 64% ≥6x/wk; Excluded from study or analysis: missing data on one or more measures | Exposure:; Breakfast frequency (≤2, 3–5, ≥6x/wk); Assessment methods and timing:; - Children were asked about number of meal times; - At baseline; Outcomes and assessment methods:; - At baseline, 1y follow-up; - Weight, height, waist circumference, and body fat (bioimpedance) were measured by study personnel. Weight and height were used to calculate BMI. Overweight (≥85th percentile) and obesity (≥95th percentile) were based on Korean CDC standard growth charts. | [underlined: Weight status (% normal weight, overweight, obesity) at 1y follow-up], unadjusted analysis; ≤2x/wk: 20.7, 17.5, 8.7; 3–5x/wk: 31.0, 7.5, 21.7; ≥6x/wk: 48.3, 75.0, 69.6; p=0.103; [underlined: Overweight at 1y follow-up], OR (95% CI); ≤2x/wk: REF; 3–5x/wk: 0.66 (0.10, 4.40), p=0.663; ≥6x/wk: 2.33 (0.56, 9.67), p=0.244; [underlined: Obesity at 1y follow-up], OR (95% CI); ≤2x/wk: REF; 3–5x/wk: 2.56 (0.26, 25.09), p=0.419; ≥6x/wk: 3.90 (0.55, 27.74), p=0.174 | Model adjustments:; - TEI: no; - Key confounders: sex, age, anthropometry at baseline; - Other:; Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position, physical activity; - Exposure data only assessed at baseline leading to a concern that changes in exposure status occurred over 1y f/u; - No evidence whether the result was biased due to missing data; - No preregistered data analysis plan; - Did not report results for some outcomes measured; - Water was not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; National Research Foundation for Korea
Libuy, 2021^38^; PCS, Millennium Cohort Study, UK; Analytic N=6,883; Study objective: To examine the extent to which inequalities in overweight, obesity, BMI and body fat over this period are consistent with the evolution of inequalities in health behaviours, including exercise and healthy diet markers; Participant characteristics at baseline: children; - Age: 5y; - Female: 50%; - Race and/or ethnicity: White: 90%; Black or Black British: 2%; Indian: 2%; Pakistani and Bangladeshi: 3%; Mixed: 2%; Other Ethnic Group: 1%; - Socioeconomic position: Equivalized weekly family income: 389; - Anthropometry: NR; - Physical activity: NR; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: NR; Excluded from study or analysis: non-singletons; missing data | Exposure:; Weekly frequency of breakfast (never vs. irregular vs. regular); Eating breakfast every day of the week is considered to be ‘regular’ consumption, with ‘irregular’ capturing some days but not all, and the category ‘never’ picking up those who skip breakfast.; Assessment methods and timing:; - Questionnaire; - At baseline; Outcomes and assessment methods:; - At baseline, 12y follow-up; - Height and weight were measured by study personnel and used to calculate BMI. Body fat was measured using bioelectrical impedance. | [underlined: Body fat % at 17y], Fixed effect estimate (95% CI) Never: REF; Irregular: −0.59 ( −1.22, 0.05), p<0.05; Regular: −1.44 (−2.08, −0.80), p<0.01; [underlined: BMI (kg/m^2^) at 17y], Fixed effect estimate (95% CI) Never: REF; Irregular: −0.02 (−0.33, 0.28); Regular: −0.15 (−0.46, 0.15) | Model adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position; - Other: region; rural status; number of siblings; employment status; annual local unemployment rates; Limitations:; - Did not account for key confounders: anthropometry at baseline, physical activity; - Exposure was subject to measurement error; - No preregistered data analysis plan; - Water was not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; Economic and Social Research Council and a consortium of government departments
Liechty, 2015^39^; PCS, National Longitudinal Study of Adolescent to Adult Health, U.S.; Analytic N=13,568; Study objective: To examine the longitudinal effects of body size over- and underestimation and other psychosocial factors on the risk for onset of overweight or obesity 1 year later among US adolescents.; Participant characteristics at baseline: adolescents; - Age: 15.8 (1.6)y; - Female: 50%; - Race and/or ethnicity: White: 65%; Black: 16%; Asian: 4%; American Indian: 2%, Other: 1%; Hispanic: 12%; - Socioeconomic position: 46% HS or less; - Anthropometry: 14% overweight; 10% obesity; - Physical activity: 41% TV time >2h/d; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: Skipping breakfast: 19%; Excluded from study or analysis: missing outcome data | Exposure:; Breakfast skipping (yes/no); Assessment methods and timing:; - "What do you usually have for breakfast on a weekday morning?" Response options included a wide range of food items and ‘nothing.’ Breakfast skipping was coded ‘1’ if participants marked they usually ate ‘nothing.’; - At baseline; Outcomes and assessment methods:; - At baseline, 1y follow-up; - Height and weight were self-reported at baseline and measured at follow-up, and used to calculate BMI. CDC growth charts were used to calculate age/sex-specific BMI percentiles, which were used to classify weight status: underweight (BMI <5th percentile); Healthy weight (BMI 5th to 85th percentile); Overweight (BMI 85th to 95th percentile); Obesity (BMI ≥95th percentile) | [underlined: Overweight at 1y], RR (95% CI) Males: 0.78 (0.49, 1.24), p=0.30; Females: 1.44 (1.00, 2.07), p=0.048; [underlined: Obesity at 1y], RR (95% CI) Males: 1.39 (0.87, 2.21), p=0.17; Females: 0.73 (0.47, 1.13), p=0.16 | Model adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline; - Other: family structure; Limitations:; - Did not account for key confounders: physical activity; - Exposure was not well defined, only measured on weekdays and subject to measurement error; - Did not provide evidence as to whether the result was unbiased due to missing data; - Outcomes were self-reported; - No preregistered data analysis plan; - Water was not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; University of Illinois; NICHD
Lipsky, 2015^40^; PCS, NEXT Generation Health Study, U.S.; Analytic N=2,785; Study objective: To examine trajectories and predictors of eating behaviors in U.S. youth from age 16–20 years, and evaluated longitudinal associations of eating behaviors with weight outcomes.; Participant characteristics at baseline: 10th graders; - Age: 16.3 (0.03)y; - Female: 55%; - Race and/or ethnicity: Non-Hispanic White: 56%; Non-Hispanic Black: 20%; Other: 5%; Hispanic: 19%; - Socioeconomic position: Parent education: 34% high school or less, 39% some college, 15% Bachelor's degree, 12% graduate degree; 5.41 (0.11) on 7-point family affluence scale; - Anthropometry: BMI 23.74 (0.18) kg/m^2^; 19% overweight; 20% obesity; - Physical activity: 3 hrs/wk vigorous physical activity; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: Breakfast, 4.45 (0.11) days/wk; Excluded from study or analysis: NR | Exposure:; Breakfast (days/wk); Assessment methods and timing:; - “How often do you usually have breakfast (more than a glass of milk or fruit juice)?”, responses ranged from never to every day.; - At baseline (wave 1), and annually until wave 4; Outcomes and assessment methods:; - At baseline (wave 1), and annually until wave 4; - Height and weight were self-reported and used to calculate BMI. | [underlined: Time-varying BMI (kg/m^2^) by time-varying breakfast (days/wk)], β (SE); −0.05 (0.05), p=0.25; [underlined: Change in BMI (kg/m^2^) over 1y by breakfast intake], β (SE); Retrospective (current BMI - previous wave BMI): 0.02 (0.02), p=0.27; Prospective (next wave BMI - current BMI): 0.02 (0.02), p=0.43 | Model adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, physical activity; - Other: school urbanicity (urban, suburban, rural); wave; complex sampling design; Limitations:; - Exposure was not well defined, subject to measurement error; - Outcomes were self-reported; - No preregistered data analysis plan; - Water was not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; NICHD; NHLBI; NIAAA; MCHB of the HRSA; NIDA
MacFarlane, 2009^41^; PCS, Health, Eating and Play Study (HEAPS), Australia; Analytic N=293; Study objective: To examine whether aspects of the family food environment were associated with body mass index z-score and weight status in children, cross-sectionally and prospectively over 3 years.; Participant characteristics at baseline: elementary school children; - Age: 5–6y, 10–12y; - Female: 50%; - Race and/or ethnicity: NR; - Socioeconomic position: Completed high school: 34%, Attended university: 47%; - Anthropometry: 19% overweight or obesity; - Physical activity: NR; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: 9% breakfast skipping; Excluded from study or analysis: missing data on covariates or BMI | Exposure:; Breakfast (daily vs. less than daily); Assessment methods and timing:; - "How often in the past few months did your child eat breakfast at home?" ‘every day’, ‘about 4–6 times/week’, ‘about 2–3 times/week’, ‘once a week’, ‘less than once/week’, ‘never or rarely’ Responses for ‘child eats breakfast at home’ were collapsed into two categories: daily and <daily.; - At baseline; Outcomes and assessment methods:; - At baseline, 3y follow-up; - Height and weight were measured by study personnel and used to calculate BMI. BMI z-scores were generated using the 2000 CDC growth chart. Change in BMI z-score was calculated. Children were classified as non-overweight or overweight/obese according to IOTF age- and sex-specific BMI cut-off points | [underlined: BMIZ at 3y follow up by baseline breakfast], β (95% CI); Daily breakfast: REF; <Daily breakfast:; 5–6y cohort: 0.3 (−0.2, 0.7), p=NS; 10–12y cohort: 0.3(−0.3, 0.9), p=NS; [underlined: Overweight and obesity at 3y follow up by baseline breakfast], OR (95% CI); Daily breakfast: REF; <Daily breakfast:; 5–6y cohort: 1.2 (0.3, 4.4), p=NS; 10–12y cohort: 2.2 (1.1, 4.7), p<0.05 | Model adjustments:; - TEI: no; - Key confounders: sex, age, socioeconomic position, anthropometry at baseline, physical activity; - Other: maternal BMI; TV viewing; clustering by school; Limitations:; - Did not account for key confounders: race and/or ethnicity; - Exposure was not well defined, only measured breakfast at home, and was subject to measurement error; - No preregistered data analysis plan; - Water was not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; Victorian Health Promotion Foundation and the Australian Research Council
MacFarlane, 2009^41^; PCS, Health, Eating and Play Study (HEAPS), Australia; Analytic N=293; Study objective: To examine whether aspects of the family food environment were associated with body mass index z-score and weight status in children, cross-sectionally and prospectively over 3 years.; Participant characteristics at baseline: elementary school children; - Age: 5–6y, 10–12y; - Female: 50%; - Race and/or ethnicity: NR; - Socioeconomic position: Completed high school: 34%, Attended university: 47%; - Anthropometry: 19% overweight or obesity; - Physical activity: NR; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: 9% breakfast skipping; Excluded from study or analysis: missing data on covariates or BMI | Exposure:; Breakfast (daily vs. less than daily); Assessment methods and timing:; - "How often in the past few months did your child eat breakfast at home?" ‘every day’, ‘about 4–6 times/week’, ‘about 2–3 times/week’, ‘once a week’, ‘less than once/week’, ‘never or rarely’ Responses for ‘child eats breakfast at home’ were collapsed into two categories: daily and <daily.; - At baseline; Outcomes and assessment methods:; - At baseline, 3y follow-up; - Height and weight were measured by study personnel and used to calculate BMI. BMI z-scores were generated using the 2000 CDC growth chart. Change in BMI z-score was calculated. Children were classified as non-overweight or overweight/obese according to IOTF age- and sex-specific BMI cut-off points | [underlined: BMIZ at 3y follow up by baseline breakfast], β (95% CI); Daily breakfast: REF; <Daily breakfast:; 5–6y cohort: 0.3 (−0.2, 0.7), p=NS; 10–12y cohort: 0.3(−0.3, 0.9), p=NS; [underlined: Overweight and obesity at 3y follow up by baseline breakfast], OR (95% CI); Daily breakfast: REF; <Daily breakfast:; 5–6y cohort: 1.2 (0.3, 4.4), p=NS; 10–12y cohort: 2.2 (1.1, 4.7), p<0.05 | Model adjustments:; - TEI: no; - Key confounders: sex, age, socioeconomic position, anthropometry at baseline, physical activity; - Other: maternal BMI; TV viewing; clustering by school; Limitations:; - Did not account for key confounders: race and/or ethnicity; - Exposure was not well defined, only measured breakfast at home, and was subject to measurement error; - No preregistered data analysis plan; - Water was not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; Victorian Health Promotion Foundation and the Australian Research Council
Narla, 2019^45^; PCS, NHLBI Growth and Health Study, U.S.; Analytic N=2,024; Study objective: To rank the importance of potentially modifiable psychosocial, dietary, behavioral and environmental risk and protective factors for female adolescent obesity; Participant characteristics at baseline: Black and White adolescent females; - Age: 10y; - Female: 100%; - Race and/or ethnicity: White: 48%; Black: 52%; - Socioeconomic position: Parental education: 24%<high school, 36% college graduate; 40% post-graduate; Household income 16%≤$9,999; 13.5% $10k–19,999; 29% $20k-39,999; 36% ≥$40k; 5.5% not available; - Anthropometry: BMI 18.5 kg/m^2^; - Physical activity: NR; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: NR; Excluded from study or analysis: missing outcome data | Exposure:; Eats breakfast (yes/no); Assessment methods and timing:; - 3d food diary (included 1 weekend day); - At baseline (age 9–10y); Outcomes and assessment methods:; - At baseline, and 10y follow-up (age 19y); - Body fat percentage was measured by sum of skinfolds measured by study personnel | [underlined: Body fat % at 10y follow-up by eating breakfast at baseline], β (SE); −2.14 (0.85), p=0.03 | Model adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline; - Other: parent education; Limitations:; - Did not account for key confounders: physical activity; - Exposure data only assessed at baseline leading to a concern that changes in exposure status occurred over f/u; - Exposure were not well defined and subject to measurement error; - No preregistered data analysis plan; - Water/beverages were not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; Stanford Medical Scholars Program; NIA
Neumark-Sztainer, 2007^46^; PCS, Project EAT, U.S.; Analytic N=2,380; Study objective: To examine the prevalence of adolescent overweight, binge eating, and use of extreme weight-control behaviors, and their simultaneous occurrence.; Participant characteristics at baseline: ethnically and socioeconomically diverse adolescents; - Age: 12.8 (0.8)y −15.8 (0.8)y; - Female: 55%; - Race and/or ethnicity: White: 49%; African American: 19%; Asian: 19%; Native American: 3%, Mixed or other: 4%; Hispanic: 6%; - Socioeconomic position: NR; 37% of low or low-middle SES; - Anthropometry: ~25% overweight; - Physical activity: NR; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: NR; Excluded from study or analysis: missing data | Exposure:; Breakfast (days/wk); Assessment methods and timing:; - “During the past week, how many days did you eat breakfast/lunch/dinner?”; - At baseline; Outcomes and assessment methods:; - At baseline, 5y follow-up; - Height and weight were self-reported and BMI was calculated. Adolescents with BMI values above the 85th percentile for gender and age were classified as overweight. | [underlined: Overweight at 5y follow-up based on baseline breakfast frequency], OR; Girls: 0.96, p=0.204; Boys: 0.92, p=0.012 | Model adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline; - Other:; Limitations:; - Did not account for key confounders: physical activity; - Exposure data only assessed at baseline leading to a concern that changes in exposure status occurred over f/u; - No information on non-completers; - Outcomes were self-reported; - No preregistered data analysis plan; - Water was not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; Maternal and Child Health Bureau
Niemeier, 2006^47^; PCS, National Longitudinal Study of Adolescent Health, U.S.; Analytic N=9,919; Study objective: To investigate whether fast food consumption and breakfast skipping are associated with weight gain during the transition from adolescence to adulthood; Participant characteristics at baseline: 7–12th grade students; - Age: 15.9 (0.11) y; - Female: NR; - Race and/or ethnicity: White: 66%; African American: 15%; Asian: 4%; Native American: 2%; Other: 1%; Hispanic: 12%; - Socioeconomic position: 64% with at least one parent with some college education; - Anthropometry: BMI 22.9 (0.12) kg/m^2^; - Physical activity: NR; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: Breakfast: 4.34 (0.06) d/wk; Excluded from study or analysis: lost to follow-up; missing data; seriously disabled respondents; pregnant females | Exposure:; Breakfast (days/wk); Assessment methods and timing:; - “In the last 7 days, on how many days did you eat breakfast?” Responses ranged from 0 to 7 days. Change in breakfast consumption was calculated from baseline to follow-up; - At baseline, 5y follow-up; Outcomes and assessment methods:; - At baseline, 5y follow-up; - Height and weight were measured by study personnel; self-reported height and weight were used for those who refused measurement/could not be measured (n=575). BMI was calculated from height and weight data. BMI z-scores were calculated based on 2000 CDC growth charts. Overweight was defined as BMI >95th percentile in adolescents, obesity was classified as BMI >30 kg/m^2^ in adults. | [underlined: BMIz at 5y follow-up], β (SE); By baseline breakfast: −0.02 (0.01), p<0.001 By 5y change in breakfast: −0.01 (0.00), p<0.01 | Model adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, physical activity; - Other: sedentary behavior; maternal obesity; month of interview; Limitations:; - Exposure was subject to measurement error; - Did not provide evidence as to whether the result was unbiased due to missing data; - No preregistered data analysis plan; - Water was not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; NICHD
Okada, 2018^51^; PCS, Longitudinal Survey of Newborns in the 21st Century, Japan; Analytic N=43,663; Study objective: To assess the association between parents who skip their breakfast and the risk of children skipping their breakfast, as well as the risk of childhood overweight/obesity in children who skip their breakfast; Participant characteristics at baseline: all babies born in Japan from Jan-July 2001; - Age: 2.5y; - Female: 48%; - Race and/or ethnicity: NR, likely majority Asian; - Socioeconomic position: 45% maternal education under high school; - Anthropometry: NR; - Physical activity: NR; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: 12% breakfast skipping; Excluded from study or analysis: lost to follow-up | Exposure:; Breakfast skipping (yes/no); Assessment methods and timing:; - “Has your child skipped breakfast? Yes or No.” (3rd and 4th surveys); “Has your child skipped breakfast? Yes (usually or sometimes) or No (never)” (5th survey); “Does your child usually skip breakfast? Yes (usually or sometimes) or No (rarely/ not at all)” (7th and 8th); “Does your child usually eat breakfast? Yes (no breakfast skipping) or No (breakfast skipping)” (9th and 10th surveys); “Do you usually eat breakfast? Yes (no breakfast skipping) or No (breakfast skipping)” (11th and 12th surveys); - At baseline (1.5y) and annually for 10 follow-ups (until 12y); Outcomes and assessment methods:; - At baseline (1.5y) and annually for 10 follow-ups (until 12y); - Height and weight were reported by parents and used to calculate BMI. Overweight and obesity were defined as BMI ≥25 kg/m^2^ | [underlined: Overweight and obesity], OR (95% CI); At 4.5y based on breakfast skipping at 2.5y: 1.00 (0.88, 1.13); at 3.5y, 1.18 (1.05, 1.32); At 5.5y based on breakfast skipping at 2.5y: 1.12 (1.00, 1.27); at 3.5y, 1.23 (1.10, 1.38); at 4.5y, 1.33 (1.21, 1.47); At 7y based on breakfast skipping at 2.5y: 1.29 (1.15, 1.44); at 3.5y, 1.45 (1.30, 1.61); at 4.5y, 1.46 (1.33, 1.60); At 8y based on breakfast skipping at 2.5y: 1.31 (1.17, 1.46); at 3.5y, 1.38 (1.25, 1.53); at 4.5y, 1.57 (1.44, 1.72); at 7y, 1.46 (1.22, 1.75); At 9y based on breakfast skipping at 2.5y: 1.25 (1.13, 1.39); at 3.5y, 1.31 (1.18, 1.45); at 4.5y, 1.62 (1.48, 1.76); at 7y, 1.58 (1.33, 1.88); at 8y, 1.57 (1.32, 1.86); At 10y based on breakfast skipping at 2.5y: 1.24 (1.11, 1.38); at 3.5y, 1.36 (1.23, 1.51); at 4.5y, 1.63 (1.50, 1.78); at 7y, 1.52 (1.28, 1.81); at 8y, 1.56 (1.31, 1.85); at 9y, 2.04 (1.47–2.82); At 11y based on breakfast skipping at 2.5y: 1.33 (1.19, 1.48); at 3.5y, 1.45 (1.31, 1.60); at 4.5y, 1.72 (1.57, 1.87); at 7y, 1.54 (1.28, 1.84); at 8y, 1.80 (1.52, 2.14); at 9y, 2.16 (1.55, 2.99); At 12y based on breakfast skipping at 2.5y: 1.35 (1.21, 1.51); at 3.5y, 1.47 (1.32, 1.64); at 4.5y,1.69 (1.55, 1.85); at 7y, 1.67 (1.39, 2.00); at 8y, 1.84 (1.55, 2.19); at 9y, 1.94 (1.36, 2.76) | Model adjustments:; - TEI: no; - Key confounders: sex, age, socioeconomic position; - Other: birth weight; feeding status and hospital admission history; parental working status; Limitations:; - Did not account for key confounders: race and/or ethnicity, anthropometry at baseline, physical activity; - Exposure was not well defined, was measured using different questions at each time point, and was subject to measurement error; - Did not provide evidence as to whether the result was unbiased due to missing data; - Outcomes were self-reported; - No preregistered data analysis plan; - Water was not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; Japan Society for the Promotion of Science
Quick, 2013^54^; PCS, Project EAT, U.S.; Analytic N=2,134; Study objective: To identify 10-year longitudinal predictors of overweight incidence during the transition from adolescence to young adulthood; Participant characteristics at baseline: diverse adolescent population; - Age: 15 (1.6)y; - Female: 53%; - Race and/or ethnicity: White: 49%; Black: 18%; Asian: 18%; Native American: 3%; Other: 5%; Hispanic: 6%; - Socioeconomic position: NR; Low income: 16%; - Anthropometry: 25% overweight; - Physical activity: ~6.8 (4.5) hr/wk MVPA; - Smoking: NR; - TEI: ~2000 (1000) kcal/d; - Habitual diet at baseline: breakfast ~4 times/wk; Excluded from study or analysis: missing data at baseline or follow-up; not overweight at baseline | Exposure:; Breakfast (days/wk); Assessment methods and timing:; - “During the past week, how many days did you eat breakfast/lunch/dinner?”; - At baseline, 10y follow-up; Outcomes and assessment methods:; - At baseline, 10y follow-up; - Self-reported height and weight were used to calculate BMI. Weight status at Time 3 was defined according to current BMI guidelines for adults (overweight: BMI ≥25 kg/m^2^) | [underlined: Overweight at 10y follow-up], OR (95% CI); Based on baseline breakfast frequency; Females: 0.91 (0.86, 0.97), p<0.05; Males: 0.95 (0.90, 1.01); Based on 10y change in breakfast frequency; Females: 0.97 (0.91, 1.04); Males: 1.02 (0.95, 1.09) | Model adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline; - Other: time 1 predictor variable; Limitations:; - Did not account for key confounders: physical activity; - Did not provide evidence as to whether the result was unbiased due to missing data; - Outcomes were self-reported; - No preregistered data analysis plan; - Water was not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; NHLBI
Seum, 2022^58^; PCS, BELLA study (module on mental health and well-being within the German Health Interview and Examination Survey for Children and Adolescents), Germany; Analytic N=460; Study objective: To examine the association of parental education as an indicator of the socioeconomic status on children's and adolescentߣs body mass index and the role of behavioral and psychological risk factors for a higher BMI longitudinally.; Participant characteristics at baseline: children and adolescents 11–17y; - Age: 14.0 (1.84); - Female: 53%; - Race and/or ethnicity: 6.5% migration status (immigrated from another country and ≥1 parent not born in Germany, or both parents immigrated and/or had non-German citizenship); - Socioeconomic position: 13.77 (2.3)y parent education; - Anthropometry: BMI 22.6 (3.98) kg/m^2^; - Physical activity: 3.93 (1.78) days/wk; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: Breakfast: 3.94 (1.76) days/weekdays; Excluded from study or analysis: missing data | Exposure:; Breakfast consumption (days/wk); Assessment methods and timing:; - Asked about on how many weekdays they eat breakfast at home. Possible responses were scored the following: 5 = Yes, always, 3.5 = Yes, 3 to 4 times a week, 1.5 = Yes, 1 to 2 times a week, 0 = Never.; - At baseline (2009–2012); Outcomes and assessment methods:; - At ~5y follow-up (2014–2017); - Height and weight were measured by study personnel and used to calculate BMI. | [underlined: BMI (kg/m^2^) at 5y follow-up based on baseline breakfast], β (95% CI); −0.36 (−0.56, −0.15), p<0.001 | Model adjustments:; - TEI: no; - Key confounders: sex, age, socioeconomic position; - Other: migration status; Limitations:; - Did not account for key confounders: race and/or ethnicity, anthropometry at baseline, physical activity; - Exposure was not well defined and was subject to measurement error; - Outcomes were only measured at f/u; - No preregistered data analysis plan; - Water was not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; German Federal Ministry of Health
Shang, 2020^59^; PCS, Secondary analysis of NISCOC cluster RCT, China; Analytic N=6,964; Study objective: To examine the association of breakfast habits and changes in cardiometabolic markers; Participant characteristics at baseline: children from an RCT on childhood obesity; - Age: 9.5 (1.2)y; - Female: 49%; - Race and/or ethnicity: NR, likely majority Asian; - Socioeconomic position: 80% with both parents <13y education; 11% household income <750 RMB/mo; - Anthropometry: BMI ~17.0 kg/m^2^; - Physical activity: MET ~623; - Smoking: NR; - TEI: ~1300 kcal/d; - Habitual diet at baseline: Breakfast frequency at 6–13y: 2.2% 0 d/wk, 14.0% 1–6 d/wk, 83.8% 7 d/wk; Excluded from study or analysis: lost to follow-up; missing data | Exposure:; Breakfast (0 days/wk, 1–6 days/wk, daily); Assessment methods and timing:; - “How many days over the past week did you have breakfast?” children were categorized into three groups: skippers (did not eat breakfast), semi-skippers (ate breakfast 1–6 times/week), and non-skippers (ate breakfast 7 times/week); - At baseline, 1y follow-up; Outcomes and assessment methods:; - At baseline, 1y follow-up; - Height and weight were measured by study personnel and used to calculate BMI. Waist circumference was measured by study personnel. Body fat % was measured using bioelectrical impedance. | [underlined: Change in BMIz over 1y], Mean (SE); 0 days/wk: 0.14 (0.05); 1–6 days/wk: 0.11 (0.02); Daily: 0.11 (0.01); p-trend=0.48; [underlined: Change in WC (cm) over 1y], Mean (SE); 0 days/wk: 3.68 (0.31); 1–6 days/wk: 3.24 (0.13); Daily: 3.32 (0.07); p-trend=0.82; [underlined: Change in WC z-score over 1y], Mean (SE); 0 days/wk: 0.24 (0.04); 1–6 days/wk: 0.20 (0.02); Daily: 0.20 (0.01); p-trend=0.53; [underlined: Change in fat mass % over 1y], Mean (SE); 0 days/wk: 0.99 (0.31); 1–6 days/wk: 0.68 (0.16); Daily: 0.69 (0.12); p-trend=0.58; [underlined: Change in fat mass % z-score over 1y], Mean (SE); 0 days/wk: 0.29 (0.07); 1–6 days/wk: 0.22 (0.03); Daily: 0.23 (0.03); p-trend=0.63; [underlined: Change in BMI (kg/m^2^) over 1y], Mean (SE); 0 days/wk: 0.85 (0.15); 1–6 days/wk: 0.69 (0.07); Daily: 0.69 (0.04); p-trend=0.52; Consistent results in multiple imputation analyses | Model adjustments:; - TEI: yes; - Key confounders: sex, age, anthropometry at baseline, physical activity; - Other: grade; center (intervention or control); baseline cardiometabolic markers of interest as fixed effects and classes in schools as random effects; Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position; - Exposure was subject to measurement error; - High attrition; - No preregistered data analysis plan; - Water was not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; China Ministry of Science & Technology
Smith, 2010^60^; PCS, Childhood Determinants of Adult Health Study, Australia; Analytic N=1,723; Study objective: To examine longitudinal associations of breakfast skipping in childhood and adulthood with cardiometabolic risk factors in adulthood; Participant characteristics at baseline: participants from a nationally representative survey; - Age: 9–15y; - Female: 53%; - Race and/or ethnicity: 92% mothers born in Australia; - Socioeconomic position: 45% with low or medium SES; - Anthropometry: 9% overweight or obesity; - Physical activity: NR; 43% <1 hr/wk leisure time physical activity in adulthood; - Smoking: 56% no childhood smoking; - TEI: NR; - Habitual diet at baseline: 86% consumed breakfast in childhood; Excluded from study or analysis: lost to follow-up; missing data; pregnant women | Exposure:; Breakfast skipping: no breakfast skipping as a child or adult, skipped breakfast as a child, skipped breakfast as an adult, skipped breakfast as a child and adult; Assessment methods and timing:; - At baseline, children reported yes/no to the question: “Do you usually eat something before school?" At follow-up, adults completed a FFQ. Breakfast skipping was defined in childhood as not usually eating before school and in adulthood as not eating between 6–9am on the day before the questionnaire was completed. Participants were classified into 1 of 4 breakfast skipping groups: “neither” (did not skip breakfast in childhood or adulthood), “as a child” (skipped breakfast in childhood), “as an adult” (skipped breakfast in adulthood), or “both” (skipped breakfast in both childhood and adulthood).; - At baseline, 21y follow-up; Outcomes and assessment methods:; - At baseline, 21y follow-up; - Height and weight were measured by study personnel and used to calculate BMI. Waist circumference was measured by study personnel. | [underlined: Waist circumference (cm) at 21y follow-up], β (95% CI); No breakfast skipping as a child or adult: REF; Skipped breakfast as a child: 1.44 (−0.43, 3.30); Skipped breakfast as an adult: −0.19 ( −1.57, 1.19); Skipped breakfast as a child and adult: 3.74 (0.83, 6.65); [underlined: BMI (kg/m^2^) at 21y follow up], β (95% CI); No breakfast skipping as a child or adult: REF; Skipped breakfast as a child: 0.81 (−0.01, 1.63); Skipped breakfast as an adult: −0.03 (−0.64, 0.57); Skipped breakfast as a child and adult: 1.31 (0.03, 2.59) | Model adjustments:; - TEI: no; - Key confounders: sex, age, socioeconomic position, physical activity; - Other: occupation; adult smoking; TV viewing; childhood smoking; fruit, dairy, lean meat, takeout food; Limitations:; - Did not account for key confounders: race and/or ethnicity, anthropometry at baseline; - Exposure was not well defined, was measured using different questions at each time point, was subject to measurement error, and measured only once at each time point; - Did not provide evidence as to whether the result was unbiased due to missing data; - No preregistered data analysis plan; - Water was not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; National Health and Medical Research Council; National Heart Foundation; Tasmanian Community Fund; Veolia Environmental Services
Timlin, 2008^63^; PCS, Project EAT, U.S.; Analytic N=2,216; Study objective: To examine the association between breakfast frequency and 5-year body weight change; Participant characteristics at baseline: middle and high school students; - Age: 14.9 (1.6)y; - Female: 55%; - Race and/or ethnicity: White: 63%; Black: 10%; Asian: 18%; Native American: 3%; Other or mixed: 3%; Hispanic: 4%; - Socioeconomic position: 15% highest SES; - Anthropometry: 16% overweight or obesity; - Physical activity: 21% high strenuous physical activity; - Smoking: 10% daily; - TEI: ~1900 kcal/d; - Habitual diet at baseline: 34% breakfast daily, 14% never have breakfast; Excluded from study or analysis: lost to follow-up; missing data | Exposure:; Breakfast: daily, intermittent (1–6x/wk), never; Assessment methods and timing:; - “During the past week, how many days did you eat breakfast?” Responses included never, 1 to 2 days, 3 to 4 days, 5 to 6 days, and every day. Breakfast frequency was recoded to 3 categories: daily breakfast eaters ("daily"); irregular eaters (1–6 d/wk, "irregular"); daily skippers ("never"); - At baseline, 5y follow-up; Outcomes and assessment methods:; - At baseline, 5y follow-up; - Height and weight were self-reported and used to calculated BMI | [underlined: Change in BMI (kg/m^2^) over 5y by breakfast frequency at 5y follow-up (controlled for baseline breakfast frequency)], Mean (SE); Never: 2.2 (0.2); Intermittent: 1.9 (0.09); Daily: 1.7 (0.17); Intermittent vs Daily: p=NS Never vs Daily: p=NS | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, physical activity; - Other: cigarette and liquor use; carbohydrates and fiber; percentage of total calories from saturated, polyunsaturated, and monounsaturated fat; individual food items (milk, cold cereal, juices, and wheat bread); psychosocial variables (being too rushed to eat, dieting in the past year, skipping meals to control weight, concern about current weight, being teased about weight, skipping meals, and eating little in the past year to control weight); Limitations:; - Exposure was subject to measurement error; - No preregistered data analysis plan; - Outcomes were self-reported; - Did not provide evidence as to whether the result was unbiased due to missing data; - Water was not accounted for in exposure assessment; Funding:; NR
Tin, 2011^64^; PCS, Hong Kong Department of Health Student Health Service, China; Analytic N=68,606; Study objective: To examine associations between breakfast location, breakfast skipping and BMI change; Participant characteristics at baseline: 4th graders participating in an annual health examination survey; - Age: 9.9 (0.6)y; - Female: 51%; - Race and/or ethnicity: NR, likely majority Asian; - Socioeconomic position: 72% parents with ≥secondary school education; Highest parental education, university or above: ~9%; 97% with at least 1 employed parent; - Anthropometry: BMI 17.3 (2.9) kg/m^2^; ~23% with overweight or obesity; - Physical activity: NR; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: 5% breakfast skipping; Excluded from study or analysis: lost to follow-up; missing data | Exposure:; Breakfast (eaters vs skippers); Assessment methods and timing:; - Single close-ended question with 4 responses ("I usually have breakfast at..."). Children who chose ‘home’, ‘fast food stall/cafeteria/restaurant’ or ‘some other places’ in response were classified as "breakfast eaters" and those who chose ‘no breakfast at all’ as "breakfast skippers".; - At baseline; Outcomes and assessment methods:; - At baseline, 2y follow-up; - Height and weight were measured by study personnel and used to calculate BMI. | [underlined: Change in BMI (kg/m^2^) over 2y by breakfast at baseline], β (95% CI); Breakfast eating: REF; Breakfast skipping: 0.11 (0.07, 0.16), p<0.001 | Model adjustments:; - TEI: no; - Key confounders: sex, age, socioeconomic position, anthropometry at baseline, physical activity; - Other: pubertal development; junk food consumption; fruit/vegetabel consumption; milk consumption; lunch habit; hours TV watching; Limitations:; - Did not account for key confounders: race and/or ethnicity; - Exposure was subject to measurement error; - No preregistered data analysis plan; - Did not provide evidence as to whether the result was unbiased due to missing data; - Water was not accounted for in exposure assessment; Funding:; Health and Health Services Research Fund, Food and Health Bureau, Hong Kong SAR
Traub, 2018^66^; PCS, Secondary analyses of Baden-Württemberg Study cluster-RCT, Germany; Analytic N=1,545; Study objective: To examine whether regular breakfast and well-balanced soft drink, and screen media consumption are associated with a lower risk of overweight and obesity in schoolchildren; Participant characteristics at baseline: 1st and 2nd graders; - Age: 7.08 (0.6) y; - Female: 49%; - Race and/or ethnicity: 31% with migration background (≥1 parent born abroad or mainly speaking non-German language); - Socioeconomic position: 32% tertiary family educational level; 13% household income ≤1750 Euros; 10% single parent; - Anthropometry: BMI 15.98 (2.14) kg/m^2^; 10% with overweight, 4% with obesity; - Physical activity: 27% physically active ≥4 d/wk for ≥60 min/d; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: 13% skipping breakfast; Excluded from study or analysis: lost to follow-up; missing data | Exposure:; Breakfast skipping (yes/no); Assessment methods and timing:; - On a 4-point Likert scale, parents stated how often their children ate breakfast before going to school. The answers also were dichotomized: “Never and rarely” versus “often and always”.; - At baseline; Outcomes and assessment methods:; - At baseline, 1y follow-up; - Height, weight, and waist circumference were measured by study personnel. BMI was calculated and age- and gender specific BMI percentile cut-offs were based on German reference data (overweight: >90th percentile; obesity: >97th percentile). Waist-to-height ratio was calculated and abdominal obesity was defined as waist-to-height ratio ≥0.5 | [underlined: Change in BMIz over 1y by skipping breakfast at baseline], β (SE); 0.09 (0.03), p=0.001; [underlined: Abdominal obesity at 1y follow-up], OR (95% CI); No skipping: REF; Skipping breakfast: 2.06 (1.23, 3.47), p=0.006; [underlined: Change in waist-to-height ratio over 1y by skipping breakfast at baseline], β (SE); 0.50 (0.19), p=0.007; [underlined: Overweight at 1y follow-up], OR (95% CI); No skipping: REF; Skipping breakfast: 1.71 (1.04, 2.80), p=0.034; [underlined: Obesity at 1y follow-up], OR (95% CI); No skipping: REF; Skipping breakfast: 0.90 (0.39, 2.07), p=0.799; [underlined: Change in weight (kg) over 1y by skipping breakfast at baselin]e, β (SE); 0.39 (0.12), p<0.001; [underlined: Change in BMI percentile over 1y by skipping breakfast at baseline], β (SE); 2.01 (0.90), p=0.027; [underlined: Change in BMI (kg/m^2^) over 1y by skipping breakfast at baseline], β (SE); 0.21 (0.01), p=0.006 | Model adjustments:; - TEI: no; - Key confounders: sex, age, socioeconomic position, anthropometry at baseline; - Other: migration background; school; participation in the intervention; Limitations:; - Did not account for key confounders: race and/or ethnicity, physical activity; - Exposure was not well defined, was subject to measurement error, and measured only once at baseline; - No preregistered data analysis plan; - Water was not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; Baden-Württemberg Stiftung
van Nassau, 2014^68^; PCS, Secondary analysis of Dutch Obesity Intervention in Teenagers (DOiT), The Netherlands; Analytic N=1,486; Study objective: To evaluate the impact of the DOiT-implementation programme on adolescents’ adiposity and energy balance-related behaviours; Participant characteristics at baseline: Dutch adolescents; - Age: ~13y; - Female: 0%; - Race and/or ethnicity: NR; - Socioeconomic position: NR; - Anthropometry: BMI ~19.5 (3) kg/m^2^; 18% overweight, 3% obesity; - Physical activity: ~50 min/d sports; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: ~5.7 days/wk; Excluded from study or analysis: missing questionnaire data or measure of adiposity | Exposure:; Breakfast consumption (days/wk); Assessment methods and timing:; - Breakfast consumption measured using questionnaire, including items on what participants usually eat/drink for breakfast. “On how many days during the school week (Monday to Friday) do you eat breakfast? On how many days in the weekend (Saturday and Sunday) do you eat breakfast?”; - At baseline (Nov 2011), and ~1.5y follow-up (Apr-June 2013); Outcomes and assessment methods:; - At baseline (Nov 2011), and ~1.5y follow-up (Apr-June 2013); - BMI was calculated from measured height and weight by study personnel and converted to sex- and age-specific BMI z-scores based on IOTF criteria. Waist circumference (WC) and sum of four skinfolds were measured. | [underlined: BMIz], β (95% CI); All: 0.0083 (−0.0055, 0.022); Girls: −0.016 (−0.0026, 0.034); Boys: 0.0015 (−0.019, 0.022); [underlined: WC (cm)], β (95% CI); All: 0.048 (−0.095, 0.19); Girls: 0.011 (−0.18, 0.02); Boys: 0.066 (−0.14, 0.27); [underlined: Sum of skinfolds (mm)], β (95% CI); All: 0.41 (−0.034, 0.86); Girls: 0.33 (−0.29, 0.96); Boys: 0.55 (−0.072, 1.2) | Model adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline; - Other: intervention; Limitations:; - Did not account for key confounders: physical activity; - Exposure was subject to measurement error; - High attrition rate/missing data; - No preregistered data analysis plan; - Did not adjust for TEI; - Water was not accounted for in exposure assessment; Funding:; Dutch Heart Foundation; SNS REAAL Fonds
Viner, 2006^69^; PCS, 1970 British Birth Cohort, UK; Analytic N=5,154; Study objective: To examine whether factors common to obesity prevention programmes in adolescence, namely exercise, sedentary activities, eating behaviours and psychological factors, predict change in BMI in 'free-living' adolescents followed into adulthood; Participant characteristics at baseline: adolescents; - Age: 16y; - Female: 51%; - Race and/or ethnicity: NR; - Socioeconomic position: NR; - Anthropometry: 8% with obesity; - Physical activity: 42% higher than average participation in sports; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: 70% ate breakfast; Excluded from study or analysis: missing data | Exposure:; Ate breakfast this morning (yes/no) Weekly frequency of eating breakfast with parents (never, 1–3x/wk, daily); Assessment methods and timing:; - Children reported the number of times per week they ate breakfast with their parents, as well as whether they ate breakfast on the day of the questionnaire.; - At baseline (age 16y); Outcomes and assessment methods:; - At baseline (age 16y), and 14y follow-up (age 30y); - Weight and height were measured at 16y and self-reported at 30y. BMI z-scores (BMIz) at 16y was calculated using UK 1990 growth reference; at 30y, BMIz was calculated separately for each sex from the cohort mean and standard deviation. | [underlined: Change in BMIz from 16y to 30y], β (95% CI); Based on whether they ate breakfast that morning:; −0.01 (−0.09, 0.07), p=0.8; Based on weekly frequency of eating breakfast with parents; Never: REF; 1–3x/wk: 0.06 (−0.05, 0.16), p=0.3; Daily: −0.06 (−0.12, 0.00), p=0.10 | Model adjustments:; - TEI: no; - Key confounders: sex, age, socioeconomic position, anthropometry at baseline; - Other: none; Limitations:; - Did not account for key confounders: race and/or ethnicity, physical activity; - Exposure assessment method not validated and exposure data only assessed at baseline leading to a concern that changes in exposure status occurred over f/u; - No information on non-completers; - Outcomes were self-reported; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; NR
Wang, 2017^70^; PCS, U.S.; Analytic N=468; Study objective: To identify breakfast location patterns (frequency and place of breakfast consumption) and explore the association between breakfast patterns and weight status over time among preadolescents.; Participant characteristics at baseline: 5th graders; - Age: 5th grade; - Female: 54%; - Race and/or ethnicity: White: 17%; Black: 36%; Other: 1%; Hispanic: 47%; - Socioeconomic position: 83% eligible for free and reduced price school breakfast; - Anthropometry: 21% overweight: 32% obesity; - Physical activity: NR; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: Breakfast frequency: 0 d/wk: 3%, 1–3 d/wk: 14%, 4–5 d/wk: 15%, 6–7 d/wk: 68%; Excluded from study or analysis: lost to follow-up; missing data | Exposure:; Frequent breakfast skippers vs double breakfast eaters; - Frequent breakfast skippers: 71% reported eating breakfast 0–3 days/wk and 100% reported not eating breakfast the day before; - Double breakfast eaters: 100% reported eating breakfast 6–7 days/wk and 100% reported eating breakfast at both school and home the day before; Assessment methods and timing:; - Survey questions asking students about the average number of days per week (0–7) they eat breakfast and the location where they ate breakfast the previous day (home, school, both, or no breakfast). Latent transition analysis used to determine 6 breakfast location patterns: frequent skippers, inconsistent school eaters, inconsistent home eaters, regular home eaters, regular home eaters, and double breakfast eaters.; - At baseline, 1y and 2y follow-up; Outcomes and assessment methods:; - At baseline, 1y and 2y follow-up; - Height and weight measured by study personnel and used to calculate BMI and determine BMI percentiles | [underlined: Overweight/obesity over 2y follow up by baseline breakfast patterns], OR (95% CI); Double breakfast eaters: REF; Frequent breakfast skippers: 2.66 (1.67, 4.24); [underlined: Change in BMI (kg/m^2^) over 1y by baseline breakfast patterns]; p=NS between double breakfast compared with other groups | Model adjustments:; - TEI: no; - Key confounders: age, race and/or ethnicity, anthropometry at baseline; - Other: school clustering; year; Limitations:; - Did not account for key confounders: sex, socioeconomic position, physical activity; - Exposure was not well defined, was subject to measurement error, and measured only once at baseline; - Did not provide evidence as to whether the result was unbiased due to missing data; - No preregistered data analysis plan; - Water was not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; NICHD
Wijtzes, 2016^71^; PCS, Generation R, The Netherlands; Analytic N=5,913; Study objective: To assess the prospective associations of breakfast, lunch, and dinner skipping at age 4 years with body fat (i.e., percent fat mass, body mass index, and weight status) at age 6 years.; Participant characteristics at baseline: birth cohort; - Age: 4y; - Female: 50%; - Race and/or ethnicity: Dutch ethnic background: 56%; Other Western: 9%; Non-Western: 35%; - Socioeconomic position: 46% with mother of low or mid-low education; 52% low or middle household income; 75% with employed mother; - Anthropometry: 82% normal weight; 18% overweight; - Physical activity: NR; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: 8% skipped breakfast; Excluded from study or analysis: missing data on BMI and fat mass, 2nd or 3rd children of the same mother | Exposure:; Breakfast skipping (yes/no; categorical) Categories of breakfast skipping based on consumption at age 4y and 6y:; - Stable meal consumption (i.e., breakfast consumption at both ages); - Stable meal skipping (i.e., breakfast skipping at both ages); - Decrease in meal skipping (i.e., breakfast skipping at 4y and breakfast consumption at 6y); - Increase in meal skipping (i.e., breakfast consumption at 4y and breakfast skipping at 6y); Assessment methods and timing:; - Children’s weekly consumption of breakfast was assessed by parent questionnaire at baseline (“never,” “1–2 days per week,” “3–4 days per week,” “5–6 days per week,” and “every day” (coded as 0–5) and at 2y f/u ( weekdays (coded as 0–5) and weekend days (coded as 0–2), and the scores were summed to calculate total weekly consumption (0–7).; - At baseline, 2y follow-up; Outcomes and assessment methods:; - At baseline, 2y follow-up; - Height and weight were measured by study personnel and used to calculate BMI. BMI SDS adjusted for age and sex were constructed based on Dutch reference growth curves. Overweight/obesity was defined according to IOTF age- and sex-specific cutoff points. Fat mass was measured using DEXA | [underlined: BMI SDS at 6y], β (95% CI); Based on breakfast at 4y; Breakfast consumption: REF Breakfast skipping: 0.13 (−0.05, 0.32); Based on breakfast at 4y and 6y Stable breakfast consumption: REF; Stable breakfast skipping: 0.13 (−0.09, 0.34); Decrease in breakfast skipping: 0.12 (−0.03, 0.27); Increase in breakfast skipping: 0.01 (−0.13, 0.15); [underlined: % Fat Mass at 6y], β (95% CI); Based on breakfast at 4y Breakfast consumption: REF; Breakfast skipping: 1.38 (0.36, 2.40); Based on breakfast at 4y and 6y Stable breakfast consumption: REF; Stable breakfast skipping: 1.80 (0.75, 2.85); Decrease in breakfast skipping: 1.24 (0.56, 1.92); Increase in breakfast skipping: 0.92 (0.11, 1.74); [underlined: Overweight/Obesity at 6y], OR (95% CI); Based on breakfast at 4y; Breakfast consumption: REF Breakfast skipping: 1.28 (0.51, 3.26); Based on breakfast at 4y and 6y Stable breakfast consumption: REF; Stable breakfast skipping: 1.70 (0.60, 4.83); Decrease in breakfast skipping: 1.07 (0.54, 2.12); Increase in breakfast skipping: 1.00 (0.47 to 2.11) | Model adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, physical activity; - Other: other meal skipping behaviors; parental BMI; children's lifestyle behaviors; Limitations:; - Exposure data only assessed at baseline leading to a concern that changes in exposure status occurred over f/u; - No preregistered data analysis plan; - Water was not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; Erasmus Medical Center Rotterdam; Erasmus University Rotterdam; Netherlands Organization for Health Research and Development
Wu, 2019^72^; PCS, Taiwan Database of Children and Youth in Poverty, Taiwan; Analytic N=1,326; Study objective: To elucidate relationships between food insecurity, dietary behaviors, and weight status, stratified by gender; Participant characteristics at baseline: children from families receiving governmental subsidies or social services; - Age: ~11y; - Female: 48%; - Race and/or ethnicity: NR, likely majority Asian; - Socioeconomic position: 53% with household income ≤$15k/mo (New Taiwan Dollar); - Anthropometry: 1% underweight; 26% overweight/obesity; - Physical activity: NR; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: Breakfast 1 time/wk or less: 6%, 2–3 times/wk: 30%; 4 + times/wk: 64%; Excluded from study or analysis: missing data | Exposure:; Skipping breakfast ≤1 time/wk (yes/no); Assessment methods and timing:; - Survey questions on the regularity of having breakfast; - At baseline, 4y f/u averaged, “1 time/week or less”, “2–3 times/week”, and “4 times/week or more”; Outcomes and assessment methods:; - At 4y follow-up; - Height and weight were self-reported and used to calculate BMI and BMI percentiles. Weight status was determined, i.e. underweight (< 5th% of representative population), normal-weight (between 5th% and 85th% of representative population), and overweight/obesity (> 85th% of representative population) | [underlined: Overweight/obesity at 15y based on skipping breakfast at 11y], OR (95% CI):; Total: 1.35 (1.09, 1.67), p<0.05; Male: 1.16 (0.86, 1.56), p=NS; Female: 1.63 (1.20, 2.22), p<0.001 | Model adjustments:; - TEI: no; - Key confounders: sex, age, socioeconomic position; - Other: none; Limitations:; - Did not account for key confounders: race and/or ethnicity, anthropometry at baseline, physical activity; - Exposure was not well defined and was subject to measurement error; - Outcomes were self-reported; - Did not provide evidence as to whether the result was unbiased due to missing data; - No preregistered data analysis plan; - Water was not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; National Cheng Kung University; National Cheng Kung University Hospital; Ministry of Science and Technology
Wu, 2019^72^; PCS, Taiwan Database of Children and Youth in Poverty, Taiwan; Analytic N=1,326; Study objective: To elucidate relationships between food insecurity, dietary behaviors, and weight status, stratified by gender; Participant characteristics at baseline: children from families receiving governmental subsidies or social services; - Age: ~11y; - Female: 48%; - Race and/or ethnicity: NR, likely majority Asian; - Socioeconomic position: 53% with household income ≤$15k/mo (New Taiwan Dollar); - Anthropometry: 1% underweight; 26% overweight/obesity; - Physical activity: NR; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: Breakfast 1 time/wk or less: 6%, 2–3 times/wk: 30%; 4 + times/wk: 64%; Excluded from study or analysis: missing data | Exposure:; Skipping breakfast ≤1 time/wk (yes/no); Assessment methods and timing:; - Survey questions on the regularity of having breakfast; - At baseline, 4y f/u averaged, “1 time/week or less”, “2–3 times/week”, and “4 times/week or more”; Outcomes and assessment methods:; - At 4y follow-up; - Height and weight were self-reported and used to calculate BMI and BMI percentiles. Weight status was determined, i.e. underweight (< 5th% of representative population), normal-weight (between 5th% and 85th% of representative population), and overweight/obesity (> 85th% of representative population) | [underlined: Overweight/obesity at 15y based on skipping breakfast at 11y], OR (95% CI):; Total: 1.35 (1.09, 1.67), p<0.05; Male: 1.16 (0.86, 1.56), p=NS; Female: 1.63 (1.20, 2.22), p<0.001 | Model adjustments:; - TEI: no; - Key confounders: sex, age, socioeconomic position; - Other: none; Limitations:; - Did not account for key confounders: race and/or ethnicity, anthropometry at baseline, physical activity; - Exposure was not well defined and was subject to measurement error; - Outcomes were self-reported; - Did not provide evidence as to whether the result was unbiased due to missing data; - No preregistered data analysis plan; - Water was not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; National Cheng Kung University; National Cheng Kung University Hospital; Ministry of Science and Technology

a Abbreviations: ALT: alanine aminotransferase; AST: aspartate aminotransferase; AUD: Australian Dollar; β: beta coefficient; BMI: body mass index; BMIz: body mass index z-score; BP: blood pressure; CDC: Centers for Disease Control and Prevention; CI: confidence interval; cm: centimeter(s); d: day(s); DEXA: dual energy x-ray absorptiometry; FFQ: food frequency questionnaire; g: gram(s); GGT: gamma-glutamyl transferase; HbA1c: hemoglobin A1C; HOMA-IR: Homeostatic Model Assessment of Insulin Resistance; hr: hour(s); HR: hazard ratio; IOTF: International Obesity Task Force; IQR: interquartile range; kcal: kilocalorie(s); kg: kilogram(s); lb: pound(s); m: meter(s); MET: metabolic equivalent; min: minute(s); mm: millimeter(s); MVPA: moderate to vigorous physical activity; N/A: not applicable; NCC: nested case control study; NCI: National Cancer Institute; NHLBI: National Heart, Lung, and Blood Institute; NICHD; Eunice Kennedy Shriver National Institute of Child Health and Human Development; NIDDK: National Institute of Diabetes and Digestive and Kidney Diseases; NIH: National Institutes of Health; NISOC: nmol: nanomole; NR: not reported; NS: not significant; OR: odds ratio; PCS: prospective cohort study; Project EAT: Project Eating and Activity over Time; RCS: retrospective cohort study; REF: reference group; RMB: renminbi (Chinese yuan); RR: risk ratio; SD: standard deviation; SDS: standard deviation score; SE: standard error; SEP: socioeconomic position; SES: socioeconomic status; svg: serving(s); TAG: triacylglycerol; TEI: total energy intake; wk: week(s); x: time(s); y: year(s)

Table 19 Risk of bias for randomized controlled trial examining breakfast in children and adolescents and growth, body composition, and risk of obesity^a^

Article | Randomization | Deviations from intended interventions (effect of assignment) | Missing outcome data | Outcome measurement | Selection of the reported result | Overall risk of bias
Kim, 2021^28^ | SOME CONCERNS | LOW | LOW | LOW | HIGH | HIGH

a Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the "Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)" tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602 .) *Low risk of bias except for concerns about uncontrolled confounding.

Table 20 Risk of bias for observational studies examining breakfast in children and adolescents and growth, body composition, and risk of obesity^b^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Affenito, 2005^1^ | LOW* | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Albertson, 2007^2^ | LOW* | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Barton, 2005^4^ | LOW* | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Bel-Sarrat, 2019^5^ | SOME CONCERNS | HIGH | LOW | LOW | HIGH | LOW | HIGH | HIGH
Berkey, 2003^6^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH
Brophy, 2009^7^ | SOME CONCERNS | VERY HIGH | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | VERY HIGH
Cayres, 2018^8^ | HIGH | VERY HIGH | LOW | LOW | HIGH | LOW | HIGH | VERY HIGH
Crossman, 2006^9^ | LOW* | HIGH | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
de Winter 201610 | HIGH | HIGH | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Drenowatz, 2013^13^ | HIGH | VERY HIGH | HIGH | LOW | HIGH | LOW | SOME CONCERNS | VERY HIGH
Elgar, 2005^15^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Gingras, 2018^16^ | HIGH | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | HIGH | HIGH
Goff, 2019^17^ | HIGH | HIGH | SOME CONCERNS | LOW | HIGH | LOW | HIGH | VERY HIGH
Haerens, 2010^20^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | HIGH | SOME CONCERNS | HIGH
Haines, 2007^21^ | SOME CONCERNS | LOW | LOW | LOW | HIGH | HIGH | SOME CONCERNS | HIGH
Hassan, 2019^22^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | HIGH | HIGH
Ikeda, 2019^23^ | HIGH | HIGH | LOW | LOW | HIGH | HIGH | SOME CONCERNS | VERY HIGH
Jeans, 2022^24^ | LOW* | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Kelly, 2016^25^ | HIGH | HIGH | HIGH | LOW | SOME CONCERNS | LOW | HIGH | VERY HIGH
Kesztyus, 2016^27^ | HIGH | HIGH | LOW | LOW | VERY HIGH | LOW | HIGH | VERY HIGH
Kesztyus, 2017^26^ | HIGH | HIGH | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Kunaratnam, 2020^30^ | VERY HIGH | SOME CONCERNS | LOW | LOW | HIGH | LOW | HIGH | VERY HIGH
Kupers, 2014^31^ | HIGH | SOME CONCERNS | LOW | LOW | HIGH | LOW | HIGH | HIGH
Larson, 2018^33^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | HIGH | SOME CONCERNS | HIGH
Laska, 2012^34^ | LOW* | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Lee, 2009^36^ | LOW* | HIGH | LOW | LOW | SOME CONCERNS | LOW | HIGH | HIGH
Lee, 2018^35^ | HIGH | HIGH | SOME CONCERNS | LOW | HIGH | LOW | HIGH | VERY HIGH
Libuy, 2021^38^ | HIGH | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Liechty, 2015^39^ | SOME CONCERNS | HIGH | LOW | LOW | HIGH | HIGH | SOME CONCERNS | HIGH
Lipsky, 2015^40^ | LOW* | HIGH | LOW | LOW | SOME CONCERNS | HIGH | SOME CONCERNS | HIGH
MacFarlane, 2009^41^ | SOME CONCERNS | VERY HIGH | LOW | LOW | HIGH | LOW | HIGH | VERY HIGH
Merten, 2009^44^ | SOME CONCERNS | HIGH | LOW | LOW | HIGH | HIGH | SOME CONCERNS | HIGH
Narla, 2019^45^ | SOME CONCERNS | HIGH | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Neumark-Sztainer, 2007^46^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | HIGH | SOME CONCERNS | HIGH
Niemeier, 2006^47^ | LOW* | SOME CONCERNS | LOW | LOW | HIGH | SOME CONCERNS | SOME CONCERNS | HIGH
Okada, 2018^51^ | HIGH | VERY HIGH | LOW | LOW | HIGH | HIGH | SOME CONCERNS | VERY HIGH
Quick, 2013^54^ | SOME CONCERNS | LOW | LOW | LOW | HIGH | HIGH | SOME CONCERNS | HIGH
Seum, 2022^58^ | HIGH | VERY HIGH | LOW | LOW | HIGH | LOW | SOME CONCERNS | VERY HIGH
Shang, 2020^59^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Smith, 2010^61^ | HIGH | HIGH | SOME CONCERNS | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Timlin, 2008^63^ | LOW* | HIGH | LOW | LOW | HIGH | HIGH | SOME CONCERNS | HIGH
Tin, 2011^64^ | SOME CONCERNS | HIGH | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Traub, 2018^66^ | HIGH | HIGH | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
van Nassau, 2014^68^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Viner, 2006^69^ | HIGH | VERY HIGH | LOW | LOW | HIGH | HIGH | HIGH | VERY HIGH
Wang, 2017^70^ | HIGH | HIGH | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Wijtzes, 2016^71^ | LOW* | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Wu, 2019^72^ | HIGH | HIGH | LOW | LOW | HIGH | HIGH | SOME CONCERNS | VERY HIGH
Yaguchi-Tanaka, 2021^73^ | HIGH | HIGH | LOW | LOW | HIGH | HIGH | HIGH | VERY HIGH

b Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the "Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)" tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602 .) *Low risk of bias except for concerns about uncontrolled confounding.

Table 21 Evidence examining the relationship between breakfast in adults and older adults and body composition and risk of obesity^a^

Study and Population Characteristics | Intervention, Comparator, and Outcome(s) | Results | Study Limitations
RANDOMIZED CONTROLLED TRIALS
Dhurandhar, 2014^11^; RCT-Parallel, U.S.; Baseline N=309, Analytic N=283 (Attrition: 8%); Study objective: To determine whether advising good nutrition habits is more effective at producing weight loss if paired with advice to skip or eat breakfast; Participant characteristics at baseline: adults attempting to lose weight; - Age: ~41 (12)y; - Female: 76%; - Race and/or ethnicity: Non-Hispanic White: 48%, Hispanic White: 7%; Non-Hispanic Black: 34%, Hispanic Black: 3%; Other: 7%; - Socioeconomic position: NR; - Anthropometry: Weight ~90 (15)kg; - Physical activity: NR; - Smoking: All nonsmoker; - TEI: NR; - Habitual diet at baseline: 48% skip breakfast; Excluded from study or analysis: aged <20 or >65y, BMI <25 or >45 kg/m^2^, not interested in weight loss, begins day after 9am <5 days/wk, participation in a weight-reduction program in past 3mo, weight loss or gain ≥5% in past 6mo, taking medication affecting appetite (weight-loss drugs or antidepressant, steroid, or thyroid medication, unless dosage has been stable for ≥6mo), medication requiring food in morning, history of prior surgical procedure for weight control, current smoker or smoked <6mo before study, any major disease, score on Brief Symptom Inventory >90th% or T-score ≥63 on global severity index or on 2 of 9 symptom scales on Symptom Checklist 90-R, current eating disorder, recent or ongoing problem with drug abuse or addiction, excessive alcohol intake, night shift work, pregnancy, or breastfeeding | Intervention: Breakfast vs No Breakfast (NB) vs Control; Breakfast: received a USDA pamphlet with a handout instructing participants to consume breakfast before 10am every day; handout also provided suggestions (and no specific restrictions) of food items that might constitute a healthy breakfast; NB: received a USDA pamphlet with a handout instructing participants not to consume any calories before 11am every day, and that only water or zero-calorie beverages could be consumed from the time of waking until 11am; Control: received a USDA pamphlet “Let’s Eat for the Health of It,” describing general good nutrition habits (with no mention of breakfast); Duration: 16wk; Compliance: self-reported compliance (calculated as % of days that participants followed breakfast recommendation after determining intent when filling out the diary) was 93.6% for breakfast group and 92.4% for NB group in completers; Outcomes and assessment methods:; - At baseline, 16wk; - Weight measured by study staff | [underlined: Change in weight from baseline to 16wk (kg) stratified by typical breakfast eating habits at baseline], Mean (SD); Breakfast skippers; Control: −0.71 (1.16); NB: −0.61 (1.18); Breakfast: −0.76 (1.26); Breakfast eaters; Control: −0.53 (1.16); NB: −0.71 (1.17); Breakfast: −0.59 (1.06) p=0.77; p-interaction=0.32 | Model adjustments:; - TEI: no; Limitations:; - Water/Beverages were not accounted for in exposure assessment; - Did not adjust for TEI
Leidy, 2015^37^; RCT-Parallel, U.S.; Baseline N=67, Analytic N=54 (Attrition: 19%); Study objective: To evaluate whether longer-term consumption of normal-protein vs. high-protein breakfast meals improves appetite control, food intake, and body composition in “breakfast skipping” young people with overweight/obesity; Participant characteristics at baseline: Breakfast-skipping young adults with overweight and obesity; - Age: 19 (1)y; - Female: 59%; - Race and/or ethnicity: Caucasian: 61%; African American: 35%; Other: 4%; - Socioeconomic position: NR; - Anthropometry: BMI ~29 kg/m^2^; - Physical activity: Examined as potential confounder - NS association with study outcomes; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: Skips breakfast: ~6 days/wk; Excluded from study or analysis: age <13 and >20y, BMI <25 and ≥40 kg/m^2^; those with metabolic diseases/conditions, currently/previously on a weight loss diet; those that do not consistently skip breakfast every weekday | Intervention: High protein breakfast vs. Normal protein breakfast vs. No Breakfast (NB); Participants were either served a high protein breakfast (HP; egg and pork-rich; 35g protein; n=24), normal protein breakfast (NP; ready-to-eat-cereal-based; 13g protein; n=21), or continued breakfast skipping (No breakfast; n=9). The NP and HP groups were provided with specific breakfast meals on a weekly basis with meal preparation instructions and asked to consume these between 6–9:45am. NP and HP breakfast were matched for energy (~350 kcal) and fat content. The NB group continued their habitual practice of skipping breakfast (nothing to eat or drink besides water) before 10am.; Duration: 12wk; Compliance: Mean 98±1% (NS difference between groups) based on daily check-off logs indicating consumption at the designated times and returned containers of uneaten food; Outcomes and assessment methods:; - At baseline, 12wk follow-up; - BMI calculated from measured height and weight.; - Body composition (lean mass, fat mass, and body fat %) measured using DEXA | [underlined: Lean mass (kg)], Baseline and 12wk, Mean (SEM); NB: 55.4 (4.9), 55.2 (3.8); NP-breakfast: 49.4 (2.5), 49.6 (2.4); HP-breakfast: 53.8 (2.3), 54.1 (2.3); Time-by-group interaction: p=0.69; [underlined: Fat mass (kg)], Baseline and 12wk, Mean (SEM); NB: 27.6 (2.9), 29.2 (2.9); HP-breakfast: 31.4 (1.9), 31.5 (1.9), −0.4 (0.5); NP-breakfast: 29.7 (1.7), 29.3 (1.8), Time-by-group interaction: p=0.05; Change from baseline to 12wk:; NB: +1.6 (0.9); HP-breakfast: −0.4 (0.5); NP-breakfast: +0.3 (0.5) NB vs HP-breakfast: p=0.02 NB vs NP-breakfast: p=NS; [underlined: Body fat (%)], Baseline and 12wk, Mean (SEM); NB: 32.7 (1.9), 34.3 (2.0); NP-breakfast: 37.5 (1.2), 37.4 (1.3); HP-breakfast: 34.5 (1.2), 34.0 (1.2); Time-by-group interaction: p=0.01; Change from baseline to 12wk:; "Similar findings" to fat mass for NB vs HP-breakfast and NB vs NP-breakfast (Data NR); [underlined: BMI (kg/m^2^)], Baseline and 12wk, Mean (SEM); NB: 29.1 (1.5), 29.5 (1.5); NP-breakfast: 29.3 (1.0), 29.4 (1.0); HP-breakfast: 30.3 (0.9), 30.3 (0.9); Time-by-group interaction: p=0.56; [underlined: Weight (kcal)], Baseline and 12wk, Mean (SEM); NB: 85.6 (5.5), 86.9 (5.4); NP-breakfast: 83.2 (3.6), 83.5 (3.5); HP-breakfast: 86.0 (3.4), 85.9 (3.3); Time-by-group interaction: p=0.51 | Model adjustments:; - TEI: yes; Limitations:; - Unclear if outcome assessors were aware of intervention assignment; - No power calculation; - No preregistered data analysis plan; Funding:; Pork Checkoff
OBSERVATIONAL STUDIES
Bajerska, 2020^3^; PCS, Secondary analysis of 16wk weight loss intervention at 1yr follow-up, Poland; Analytic N=64; Study objective: To identify some of the predictors of weight regain in postmenopausal women who had lost weight a year earlier; Participant characteristics at baseline: postmenopausal women; - Age: 60.5 (0.5)y; - Female: 100%; - Race and/or ethnicity: Caucasian: 100%; - Socioeconomic position: Years of education, regainers vs maintainers: 13(1) < 15(0.5), p=0.032; 73% married; - Anthropometry: Weight before dieting: 83 (2) kg; - Physical activity: 35% <600 MET/min/wk; 51% 600–1499 MET/min/wk; 14% ≥1500 MET/min/wk; - Smoking: All nonsmokers; - TEI: Before dieting, regainers vs maintainers: 1892.7 (55.4) vs 1968.1 (58.6), p=0.053; - Habitual diet at baseline: Ate breakfast, regainers vs maintainers: 42% vs 74%, p=0.01; Excluded from study or analysis: smokers; waist circumference <80cm; premenopausal; type 2 diabetes; monogenic dyslipidemia; a history of cardiovascular disease; use of hypoglycemic, hypolipidemic, anti-inflammatory, or weight loss agents, as well as any drug known to influence liver function; with endocrine disorders or on hormonal replacement therapy; significant weight change in 6mo prior to current study, intolerance or food allergy to key components of the intervention diets, and excessive alcohol consumption (>2 drinks/day) | Exposure:; Eating Breakfast vs Skipping Breakfast; Eating Breakfast: those who reported eating breakfast 5–7 days per week; Skipping Breakfast: those who reported eating breakfast ≤4 days per week; Breakfast was defined as any meal eaten in the morning (6–9am) consisting of any type of food, including milk.; Assessment methods and timing:; - Single question ("How many days per week do you eat breakfast?"); women who reported eating breakfast 5–7 days per week were categorized as breakfast eaters, while women who reported eating breakfast ≤4 days per week were categorized as breakfast skippers. Breakfast was defined as any meal eaten in the morning (6:00–9:00) consisting of any type of food, including milk.; - At baseline of 16wk intervention, 1yr follow-up (week 68); Outcomes and assessment methods:; - 1yr follow-up (week 68); - Weight regain was assessed by calculating change in weight from baseline of the weight loss maintenance period (week 16) to 1yr follow-up (week 68). Participants were characterized as weight loss maintainers (≥5% weight loss below their baseline weight at follow-up) or weight regainers (all others).; - Weight was measured by study staff at the weight loss maintenance period (week 16), but unclear how it was measured at 1yr follow-up. | [underlined: Weight regain at 1yr], OR (95% CI) Eating breakfast (n=14): REF; Skipping breakfast (n=19): 6.345 (1.919, 33.809) p=0.030 | Model adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, anthropometry at baseline, physical activity, smoking; - Other: type of weight loss diet (intervention); Limitations:; - Did not account for key confounders: socioeconomic position; - Exposure assessment method not validated; - Breakfast skippers included those who consumed no breakfast up to 4 times/week; - Concerns with deviations from intended intervention; - Bias due to selection of participants into the study as selection occurred after exposure was measured pre-intervention; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; National Science Centre (Poland)
Elahy, 2023^14^; PCS, secondary analysis of Innovative Approaches to Diet, Exercise and Activity (IDEA) trial, U.S.; Analytic N=372; Study objective: To estimate the effect of hypothetical interventions of higher and lower frequency of breakfast and post-dinner snack consumption on changes in body weight and composition over 18 months after a successful 6mo standard behavioral weight-loss program; Participant characteristics at baseline: young adults with overweight or obesity; - Age: 30.1 (3.8)y; - Female: 71%; - Race and/or ethnicity: White: 82%; Black: 15%; Asian: 3%; - Socioeconomic position: Education: 23% high school/GED/some college, 42% bachelors degree, 35% graduate degree; Annual household income: 39% <$5k, 43% $5k-<$12k, 17% $12k-<$16k; - Anthropometry: BMI 31.7 (4) kg/m^2^; - Physical activity: <150 min/wk moderate PA: 76%; <75 min/wk vigorous PA: 35%; - Smoking: 8% current; - TEI: 1900.5 (866.7) kcal/d; - Habitual diet at baseline: 66% eat breakfast 5–7x/wk; 97% eat dinner 5–7x/wk; 34% eat post-dinner snack 5–7x/wk; Excluded from study or analysis: BMI <25 or >40 kg/m^2^; <18 or >35y; had past or planned weight loss surgery; current participation in another weight loss intervention study; incomplete questions on breakfast frequency, evening snack frequency, body composition, and weight data at baseline and 6mo follow-up; implausible energy intake (<600 or >6000 kcal/d for women and <800 or >8000 kcal/d for men) | Exposure:; Breakfast (0–4 vs 5–7 times/wk); Breakfast was implied to be the first eating occasion/meal of the day. Breakfast frequency was categorized as regular breakfast frequency (consumption of breakfast 5–7 times/wk) and irregular to rare breakfast frequency (consumption of breakfast 0–4 times/wk).; Assessment methods and timing:; - A daily meal patterns survey was used to assess frequency of meals and snacks. Participants were asked "In a typical week, how many times do you eat…?" and answers were 0, 1–2, 3–4, 5–6, and 7 times.; - At baseline (after 6mo trial), and 6-,12-, and 18-month follow-up; Outcomes and assessment methods:; - At baseline (after 6mo trial), and 18-month follow-up; - Weight was measured and body composition (fat mass and lean mass) was assessed using DEXA. Absolute changes in weight and body composition were calculated as the difference between 18-mo values and baseline values. | [underlined: Change in body fat mass (kg) over 18mo]; Per-protocol; Within groups: Mean change (95% CI); 0–4x/wk: 2.94 (0.44, 4.84); 5–7x/wk: 2.34 (1.51, 3.13); Between groups: Mean difference (95% CI); 0–4x/wk (REF) vs 5–7x/wk: −0.57 (−0.82, −0.33); Intent-to-treat; Within groups: Mean change (95% CI); 0–4x/wk: 3.38 (1.43, 5.38); 5–7x/wk: 2.45 (0.95, 3.96); Between groups: Mean difference (95% CI); 0–4x/wk (REF) vs 5–7x/wk: −1 ( −1.06, −0.95); [underlined: Change in body lean mass (kg) over 18mo]; Per-protocol; Within groups: Mean change (95% CI); 0–4x/wk: 0.62 (0.15, 1.06); 5–7x/wk: 0.61 (0.4, 0.91); Between groups: Mean difference (95% CI); 0–4x/wk (REF) vs 5–7x/wk: −0.01 (−0.06, 0.05); Intent-to-treat; Within groups: Mean change (95% CI); 0–4x/wk: 0.72 (−0.18, 1.71); 5–7x/wk: 0.56 (−0.44, 0.96); Between groups: Mean difference (95% CI); 0–4x/wk (REF) vs 5–7x/wk: 0.37 (0.34, 0.39); [underlined: Change in body weight (kg) over 18mo]; Per-protocol; Within groups: Mean change (95% CI); 0–4x/wk: 3.56 (0.67, 5.63); 5–7x/wk: 2.95 (2.01, 3.96); Between groups: Mean difference (95% CI); 0–4x/wk (REF) vs 5–7x/wk: −0.59 (−0.86, −0.32); Intent-to-treat; Within groups: Mean change (95% CI); 0–4x/wk: 4.1 (1.67, 6.48); 5–7x/wk: 3.01 (0.98, 4.13); Between groups: Mean difference (95% CI); 0–4x/wk (REF) vs 5–7x/wk: −1.39 ( −1.45, −1.33) | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, physical activity, smoking; - Other: breakfast frequency; post-dinner snack frequency; alcohol consumption; sleep duration; diet quality; depression; Limitations:; - Exposure assessment method not validated; - Water/Beverages were not accounted for in exposure assessment; Funding:; Funding NR
Goto, 2010^18^; RCS, Japan; Analytic N=4,634; Study objective: To identify lifestyle and sociodemographic risk factors for becoming overweight among male college students and to construct a self-administered tool to stratify students according to the risk of overweight based on the cohort data collected at the annual health checkups.; Participant characteristics at baseline: male college students; - Age: 21.5 (1.9)y; - Female: 0%; - Race and/or ethnicity: Japanese nationality: 98%; - Socioeconomic position: All university students; - Anthropometry: BMI 24.2 (2.3) kg/m^2^; 23% with BMI >25 kg/m^2^; - Physical activity: 42% exercise ≥2 times/wk; - Smoking: 13% current; - TEI: NR; - Habitual diet at baseline: 47% skip breakfast ≥2 times/wk; Excluded from study or analysis: BMI <22 kg/m^2^ at baseline | Exposure:; Skipping breakfast ≥2x/wk vs ≤1x/wk; Assessment methods and timing:; - Self-administered lifestyle questionnaire (details NR); - Baseline, 1yr; Outcomes and assessment methods:; - 1yr; - Weight and height measured by staff at health checkup and used to calculate BMI. Change in BMI was based on whether it was a ≥5% increase over the former year. | [underlined: ≥5% increase in BMI over 1yr], OR (95% CI) Skipping breakfast ≤1x/wk (n=274): REF Skipping breakfast ≥2x/wk (n=324): 1.34 (1.12, 1.61) p=0.002 | Model adjustments:; - TEI: no; - Key confounders: sex, anthropometry at baseline; - Other: none; Limitations:; - Did not account for key confounders: age, race and/or ethnicity, socioeconomic position, physical activity, smoking; - Exposure assessment method not validated; - Concerns with deviations from intended intervention; - Selection bias due to exclusion of those with BMI <22 kg/m^2^ at baseline; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; No external funding
Guinter, 2020^19^; PCS, Sister Study, U.S.; Analytic N=46,037; Study objective: To examine the association between breakfast consumption frequency and weight status with a focus on a regular day-to-day pattern.; Participant characteristics at baseline: women with a sister diagnosed with breast cancer; - Age: ~54 (8)y; - Female: 100%; - Race and/or ethnicity: Non-Hispanic White: 81%; Non-Hispanic Black: 10%; Other: 4%; Hispanic: 5%; - Socioeconomic position: 21% no college; 24% some college; 55% ≥college; - Anthropometry: BMI ~28 (6) kg/m^2^; - Physical activity: ~49 (31) MET-hrs/wk; - Smoking: 41% never; 34% former; 25% current; - TEI: ~1600 kcal/d; - Habitual diet at baseline: 54% ate breakfast daily; 5.4% ate breakfast <1 day/wk; Excluded from study or analysis: BMI <15 or >50 kg/m^2^; extreme caloric intake (<500 or >5000 kcal/day); reported working night shifts at baseline; missing exposure or covariate data | Exposure:; Breakfast consumption frequency (0, 1–2, 3–4, 5–6, or 7 days/wk); Participants who reported eating breakfast 3–4 days/wk (i.e., those who had the least regular pattern in breakfast consumption) served as the reference group.; Assessment methods and timing:; - "During the past year, on average, how many days per week did you eat breakfast?” Participants were told to count all beverages as snacks, except for coffee, tea, diet drinks, and water.; - At baseline; Outcomes and assessment methods:; - At baseline, 5y follow-up; - Weight was self-reported and used to calculate incident overweight (BMI ≥25 kg/m^2^), incident obesity (BMI ≥30 kg/m^2^), and incident 5 kg weight gain. | [underlined: Overweight (BMI≥25 kg/m^2^)], RR (95% CI); 0 days/wk: 0.74 (0.62, 0.89); 1–2 days/wk: 0.91 (0.78, 1.07); 3–4 days/wk: REF; 5–6 days/wk: 0.97 (0.85, 1.09); 7 days/wk: 0.88 (0.78, 0.99); [underlined: Obesity (BMI≥30 kg/m^2^)], RR (95% CI); 0 days/wk: 0.72 (0.59, 0.87); 1–2 days/wk: 0.75 (0.62, 0.89); 3–4 days/wk: REF; 5–6 days/wk: 0.91 (0.80, 1.04); 7 days/wk: 0.79 (0.70, 0.90); [underlined: [underlined: Weight gain (≥5kg)]], RR (95% CI); 0 days/wk: 1.00 (0.90, 1.11); 1–2 days/wk: 0.98 (0.89, 1.08); 3–4 days/wk: REF; 5–6 days/wk: 0.99 (0.92, 1.06); 7 days/wk: 0.97 (0.91, 1.04); Results were also provided stratified by baseline BMI and for a sensitivity analysis excluding women who participated on a weight loss diet in previous 12mo to baseline. | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, physical activity, smoking; - Other: diet quality (measured by HEI-2015); average duration of sleep; perceived stress; participation in weight loss diet over previous year; Limitations:; - Exposure data only assessed at baseline leading to a concern that changes in exposure status occurred over 5y f/u; - Outcomes were self-reported; - No preregistered data analysis plan; Funding:; NIEHS
Kito, 2019^29^; RCS, Japan; Analytic N=45,524; Study objective: To investigate whether skipping breakfast and/or having dinner before bedtime predicted the onset of obesity/overweight in men aged 20–49 years, using a follow-up survey.; Participant characteristics at baseline: men with normal weight; - Age: 34y; - Female: 0%; - Race and/or ethnicity: NR but likely majority Asian; - Socioeconomic position: All employed and with health insurance; - Anthropometry: BMI 21.6 kg/m^2^; - Physical activity: 13% exercise ≥30min for ≥2 days/wk; - Smoking: 52% current; - TEI: NR; - Habitual diet at baseline: 39% skipped breakfast ≥3 days/wk; Excluded from study or analysis: aged <20 or >49y; BMI ≥25 kg/^2^; history of stroke (e.g. cerebral hemorrhage, cerebral infarction), a history of heart disease (e.g., angina pectoris, myocardial infarction) and/or chronic renal failure; taking antihypertensive drugs, insulin injections, anti-hyperglycemic drugs or cholesterol-reducing drugs; leaving target age range during the follow-up period; missing baseline data on any of the questionnaire items (BMI, dietary habits, smoking habit, drinking frequency, exercise habit, sleep, medical history, medications); missing BMI data during follow-up | Exposure:; Skipping breakfast ≥3 days/wk (yes vs no); Assessment methods and timing:; - Health checkup data included information on lifestyle habits; details NR; - At baseline; Outcomes and assessment methods:; - At baseline, 3y follow-up; - Incident overweight/obesity (BMI ≥25 kg/m^2^) based on health checkup data | [underlined: Overweight (BMI≥25 kg/m^2^)], OR (95% CI); Breakfast: REF; Skipping Breakfast: 1.18 (1.04, 1.33) | Model adjustments:; - TEI: no; - Key confounders: sex, age, anthropometry at baseline, physical activity, smoking; - Other: eating speed; late night meals/snacking; drinking frequency; sleep habits; interaction between skipping breakfast and having dinner within 2hr of bedtime; Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position; - Exposure data only assessed at baseline leading to a concern that changes in exposure status occurred over 3y f/u; - Exposure assessment method not reported; - Selection into study maybe have been related to intervention/exposure and outcome; - No information on non-completers; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; No funding reported.
LaRose, 2019^32^; PCS, secondary analysis of Study of Novel Approaches to Weight Gain Prevention (SNAP) trial, U.S.; Analytic N=500; Study objective: To examine changes in key dietary outcomes within the SNAP Trial and explore whether improvements in these dietary behaviors were associated with more favorable weight trajectories over 2 years of follow-up.; Participant characteristics at baseline: adults aged 18–35y; - Age: 28.2 (4.4)y; - Female: 78%; - Race and/or ethnicity: Non-Hispanic White: 73%; African-American: 11%; Asian/Pacific Islander: 4%; Multiple/Refusal: 4%; Hispanic: 8% Socioeconomic position: 20% not college graduate; 80% college graduate; 63% employed full-time; 29% full-time student; 9% other; - Anthropometry: BMI 25.4 (2.6) kg/m^2^ (50% with overweight); - Physical activity: NR; - Smoking: NR; - TEI: 1663 (611) kcal/d; - Habitual diet at baseline: 4.7 (2.3) eating occasions/d; 5.6 (1.8) breakfast/wk; 48% eat breakfast daily; Excluded from study or analysis: age <18 or >35 y; BMI <21 or >30 kg/m^2^; major medical comorbidities; recent weight lost ≥10 lbs; current or planned pregnancy; no internet access; non-English speaking | Exposure:; Frequency of breakfast consumption (times/wk); Assessment methods and timing:; - Eating pattern questionnaire items assessed eating frequency over the past 30 days (exact question NR); - At baseline, 2y follow-up; Outcomes and assessment methods:; - At baseline, 2y follow-up; - Weight measured by trained research staff | [underlined: Change in weight from baseline to 4mo by change in breakfast frequency], Partial correlation; −0.06, p=0.15; [underlined: Change in weight from baseline to 2y by change in breakfast frequency], Partial correlation; −0.14, p=0.0034 | Model adjustments:; - TEI: no; - Key confounders: anthropometry at baseline; - Other: trial group assignment; Limitations:; - Did not account for key confounders: sex, age, race and/or ethnicity, socioeconomic position, physical activity, smoking; - Exposure assessment method not validated; - Post-exposure interventions may have been influenced by prior exposure during f/u; - No information on non-completers; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; - Unclear if TEI was adjusted for; Funding:; NHLBI
Larson, 2018^33^; PCS, Project EAT (Eating and Activity in Teens and Young Adults), U.S.; Analytic N=695; Study objective: To identify personal, behavioral, and environmental factors that predicted healthy weight maintenance during the transition from adolescence to adulthood and as individuals progressed from the third to fourth decade of life.; Participant characteristics at baseline: young adults; - Age: ~25y at Time 3; - Female: 45%; - Race and/or ethnicity: White: 50%; African American: 17%; Asian: 20%; Native American: 3%, Mixed or other: 5%; Hispanic: 5%; - Socioeconomic position: NR; - Anthropometry: NR; - Physical activity: NR; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: NR; Excluded from study or analysis: those without height and weight data at ≥1 timepoint; women who were pregnant when they reported their adult weight at Time 3 or 4; adults with BMI <18.5 kg/m^2^ at Time 4 | Exposure:; Breakfast (times/wk); Assessment methods and timing:; - "During the past week, how many days did you eat breakfast?" Five responses ranging from never (coded 0) to every day (coded 7).; - At baseline (Time 1, 1998–1999), 10y follow-up, (Time 3, 2008–2009), and 17y follow-up (Time 4, 2015–2016); Outcomes and assessment methods:; - At baseline (Time 1, 1998–1999), 10y follow-up, (Time 3, 2008–2009), and ~15y follow-up (Time 4, 2015–2016); - Weight and height were self-reported and used to calculate BMI. Healthy weight status (i.e., non-overweight BMI) was defined using screening guidelines: BMI <85%tile for sex and age at Time 1 and BMI <25 kg/m^2^ at Time 3 and Time 4.; - Healthy weight maintenance in early adulthood was defined by a non-overweight BMI | [underlined: Healthy weight maintenance at Time 4], OR (95% CI); By 1 SD Δ in breakfast frequency at Time 3; Women: 1.27 (0.97, 1.66); Men: 1.14 (0.86, 1.52); By 1 SD Δ in breakfast frequency from Time 3 to Time 4; Women: 0.84 (0.61, 1.15); Men: 1.24 (0.90, 1.70) | Model adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline; - Other: none; Limitations:; - Did not account for key confounders: physical activity, smoking; - Weight and height were self-reported; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; NHLBI
Martinez, 2021^42^; PCS, Mexican Teachers’ Cohort, Mexico; Analytic N=65,099; Study objective: To evaluate the association between breakfast frequency and weight change in a well-established prospective cohort of middle-aged Mexican women.; Participant characteristics at baseline: middle-age Mexican women; - Age: 42.5 (7.1)y; - Female: 100%; - Race and/or ethnicity: 7% indigenous language/dialect (likely majority Mexican); - Socioeconomic position: 74% Bachelors degree or higher; 26% lower SES, 33% middle SES, 41% upper SES; All teachers; - Anthropometry: BMI 27 (4) kg/m^2^; - Physical activity: ~32 (29) METs hr/wk; - Smoking: 75% never; 15% former; 10% current; - TEI: ~1800 (600) kcal/d; - Habitual diet at baseline: 25% consume breakfast daily; Excluded from study or analysis: women who did not give information regarding the main exposure or outcome, breakfast frequency, and incomplete self-reported body weight; cancer at baseline; being pregnant at the time of any questionnaire; those who did not respond to ≥70 items of FFQ; those with energy intake <500 or >3500 kcal/d | Exposure:; Frequency of breakfast (0, 1–3, 4–6, 7 times/wk); Assessment methods and timing:; - “How many days a week do you have a solid breakfast (in addition to coffee, juice, milk, or tea)?” and "On average, how many meals per day do you eat (taking into account food between meals)?”; - At baseline; Outcomes and assessment methods:; - At baseline (2006–2008), and ~3y follow-up (2011); - Weight was self-reported | [underlined: Change in weight over 3y], PR (95% CI); No breakfast: REF; 1–3x/wk: 0.05 (−0.08, 0.17); 4–6x/wk: 0.04 (−0.09, 0.17); 7x/wk: −0.06 (−0.19, 0.07); p-trend: 0.14; [underlined: Weight gain ≥5kg over 3y], PR (95% CI); No breakfast: REF; 1–3x/wk: 0.97 (0.94, 1.01); 4–6x/wk: 0.95 (0.91, 0.99); 7x/wk: 0.93 (0.89, 0.97); p-trend: 0.02 | Model adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, physical activity, smoking; - Other: parity; use of contraceptive hormones; menopause status; sleep; meals aways from home; scores of diet patterns (fruit and vegetables, Western and Modern Mexican); Limitations:; - Exposure data only assessed at baseline leading to a concern that changes in exposure status occurred over 3y f/u; - High attrition rate/missing data; - Weight was self-reported; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; American Institute for Cancer Research; Consejo Nacional de Ciencia y Tecnologiá (CONACyT)
Megson, 2017^43^; PCS, secondary weight , U.S.; Analytic N=211; Study objective: To examine the association between breakfast eating and eating frequency on BMI and weight loss outcomes among adults enrolled in a weight loss intervention.; Participant characteristics at baseline: adults with overweight or obesity; - Age: 47.3 (11.0)y; - Female: 83%; - Race and/or ethnicity: Non-Hispanic White: 87%; - Socioeconomic position: 92% college educated; - Anthropometry: BMI 34.2 (6.9) kg/m^2^; - Physical activity: NR; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: Eat breakfast 5.6 (2.0) days/wk; Ate meals and snacks 5.0 (2.7) meals and snacks per day (range 1–30); Excluded from study or analysis: age <18 or >70y; BMI <25 kg/m^2^; current or planned pregnancy or serious medical condition for which weight loss and regular exercise would be unsafe; no Internet access; non-English speaking | Exposure:; Breakfast frequency (0–7 days/wk); also examined categorically (increased, decreased, or had no change in breakfast eating from pre- to post-treatment); Assessment methods and timing:; - ‘‘On average, how many days per week do you eat breakfast?’’ Response options ranged from zero to seven.; - ‘‘Counting all meals and any snacks you may have, how many times a day do you usually eat?"; At baseline and 3mo follow-up (pre- and post-intervention); Outcomes and assessment methods:; - At baseline and 3mo follow-up (pre- and post-intervention); - Weight measured and used to compute overall weight loss and percentages of participants who achieved a 5% weight loss. | [underlined: Percent weight loss over 3mo by baseline breakfast frequency] β=0.06, p=0.38; [underlined: Percent weight loss over 3mo by change in breakfast frequency (days/wk) over 3mo] r=0.26, p<0.001; [underlined: Percent weight loss over 3mo by change in breakfast frequency (increase, decrease, no change) over 3mo]; Decrease (n=23) < No change (n=125): data NR (figure only), p=0.01; Decrease (n=23) < Increase (n=63): data NR (figure only), p=0.004; No change (n=125) vs Increase (n=63): data NR (figure only), p=NS; [underlined: Achieved 5% weight loss at 3mo by change in breakfast frequency (increase, decrease, no change) over 3mo]; Decrease (n=23): 21.7% Increase/No Change (n=188): 45.7% p=0.02 | Model adjustments:; - TEI: no; - Key confounders: age, anthropometry at baseline; - Other: treatment arm; Limitations:; - Did not account for key confounders: sex, race and/or ethnicity, socioeconomic position, physical activity, smoking; - Exposure assessment method not validated; - Did not describe or account for the impacts of missing data; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; NR
Nishiura, 2010^48^; PCS, Japan; Analytic N=2,632; Study objective: To investigate whether dietary patterns explain the possible association between short sleep duration and obesity.; Participant characteristics at baseline: Non-obese Japanese male workers (40–59y); - Age: ~47 (5)y; - Female: 0%; - Race and/or ethnicity: NR, but likely majority Asian; - Socioeconomic position: Majority white-collar workers; - Anthropometry: BMI ~22 (2) kg/m^2^; - Physical activity: 37% currently exercise; - Smoking: 57% current; - TEI: NR; - Habitual diet at baseline: 16% skip breakfast; 6% snack; Excluded from study or analysis: BMI >25 kg/m^2^ at baseline; missing or incomplete data at baseline; those lost at follow-up | Exposure:; Skipping breakfast (yes/no); Assessment methods and timing:; - Lifestyle questionnaire at annual health checkup, which included yes/no questions on skipping breakfast and snacking; - At baseline; Outcomes and assessment methods:; - At baseline, 4y follow-up; - Height and weight were measured at annual health exam and used to calculate BMI. Obesity was defined as BMI ≥25 kg/m^2^ based on criteria determined by Japan Society for the Study of Obesity | [underlined: Obesity (BMI≥25 kg/m^2^)], OR (95% CI); Not skipping breakfast: REF; Skipping breakfast: 1.17 (0.75, 1.83) | Model adjustments:; - TEI: no; - Key confounders: sex; - Other: none; Limitations:; - Did not account for key confounders: age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, physical activity, smoking; - Exposure assessment method not validated; - Exposure data only assessed at baseline leading to a concern that changes in exposure status occurred over 4y f/u; - High attrition rate/missing data; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; No industry funding.
Nooyens, 2005^49^; PCS, Doetinchem Cohort Study, The Netherlands; Analytic N=288; Study objective: To study changes in lifestyle in relation to changes in body weight and waist circumference associated with occupational retirement in men; Participant characteristics at baseline: older men; - Age: ~ 56 (2)y; - Female: 0%; - Race and/or ethnicity: NR; - Socioeconomic position: Higher vocational education or university: ~45% of those with sedentary occupations; ~17% of those with active occupations; 61% currently working; 39% retired; - Anthropometry: BMI ~26 kg/m^2^; 10% with obesity, 34% with abdominal obesity; - Physical activity: 46% with active occupations; - Smoking: ~75% nonsmoker; - TEI: NR; - Habitual diet at baseline: NR; Excluded from study or analysis: aged <50 or >65y; incomplete data on body weight and waist circumference; cancer, cardiovascular disease, diabetes, waist circumference <79 cm at baseline | Exposure:; Breakfast frequency (times per week); Assessment methods and timing:; - Validated semi-quantitative FFQ assessing habitual consumption during the previous year; - At baseline, 5y follow-up; Outcomes and assessment methods:; - At baseline, 5y follow-up; - Weight and waist circumference measured by staff at health center. | [underlined: Change in waist circumference (cm/yr) by change in breakfast frequency (times/wk)], β 0.10, p=0.01; [underlined: Change in weight (kg/yr) by change in breakfast frequency (times/wk)], β 0.04, p=0.21 | Model adjustments:; - TEI: yes (for WC but not weight); - Key confounders: sex, age, socioeconomic position, anthropometry at baseline, physical activity, smoking; - Other: fruit, sugared soft drinks, fiber density; potatoes (in weight analysis); pasta, alcoholic beverages, carbohydrate (in waist circumference analysis); Limitations:; - Did not account for key confounders: race and/or ethnicity; - No information on non-completers; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; Funding:; Ministry of Health, Welfare and Sport of The Netherlands; National Institute for Public Health and the Environment;; Netherlands Heart Foundation
Odegaard, 2013^50^; PCS, Coronary Artery Risk Development in Young Adults (CARDIA), U.S.; Analytic N=1138 (abdominal obesity); 1064 (obesity); Study objective: To examine breakfast intake frequency with incidence of metabolic conditions; Participant characteristics at baseline: young black and white adults; - Age: ~32(3)y; - Female: 56%; - Race and/or ethnicity: White: 54%; Black: 46%; - Socioeconomic position: Education: ~14(2)y; - Anthropometry: BMI ~26(6) kg/m^2^; - Physical activity: ~330 exercise units/wk; - Smoking: 26% current; 16% former; - TEI: ~2760 (1200) kcal/d; - Habitual diet at baseline: 43% ate breakfast 0–3 days/wk, 22% 4–6 days/wk, and 35% daily; Excluded from study or analysis: did not participate in any clinical exam in years 10–25; diabetes at baseline; missing dietary data or with reported energy intakes outside 800–8,000 kcal/day for men and 600–6,000 kcal/day for women; missing data on alcohol, smoking, or physical activity); participants prevalent with the condition at year 7 | Exposure:; Breakfast frequency (0–3, 4–6, or 7 days/wk); Assessment methods and timing:; - Interview-administered CARDIA diet history questionnaire; - Baseline (year 7), and year 20; Outcomes and assessment methods:; - Baseline (year 7), and years 10, 15, 20, and 25; - Height, weight, and waist circumference were measured by staff at each clinical examination. Obesity defined as BMI ≥30 kg/m^2^ and abdominal obesity as waist circumference >88cm for women or >102 cm for men. | [underlined: Abdominal obesity], HR (95% CI); 0–3 d/wk: REF; 4–6 d/wk: 0.84 (0.70, 0.99); 7 d/wk: 0.78 (0.66, 0.91); p-trend=0.001; [underlined: Mean increase in waist circumference from year 7–25 (cm)]; 0–3 d/wk > 4–6 d/wk: data NR (figure only); p=0.12; 0–3 d/wk > 7 d/wk: data NR (figure only); p=0.001; [underlined: Obesity], HR (95% CI); 0–3 d/wk: REF; 4–6 d/wk: 0.85 (0.71, 1.03); 7 d/wk: 0.80 (0.67, 0.96); p-trend=0.011; [underlined: Mean weight gain from year 7–25 (kg)]; 0–3 d/wk > 4–6 d/wk: data NR (figure only); p=0.06; 0–3 d/wk > 7 d/wk: 1.91, p=0.001 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, physical activity, smoking; - Other: study center; alcohol consumption; fast food restaurant use; diet quality score; frequency of lunch/dinner and morning/afternoon/evening snacks; Limitations:; - Did not account for those with missing data; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; Funding:; NHLBI; NIDDK; Bell Institute of Health and Nutrition at General Mills
Phelan, 2006^53^; PCS, National Weight Control Registry, U.S.; Analytic N=2,266; Study objective: To examine whether the diet and exercise behaviors of successful weight losers entering the National Weight Control Registry have changed between 1995 and 2003.; Participant characteristics at baseline: adults with successful weight loss; - Age: 46.9 (12.6)y; - Female: 78%; - Race and/or ethnicity: White: 95.4%; African-American: 2,1%; Asian: 0.4%; Other: 0.9%; Hispanic: 1.1%; - Socioeconomic position: Education: 29% graduate degree, 25% college or university, 34% some college, 12% ≤high school; Marital status: 64% married, 14% separated or divorced, 22% single; - Anthropometry: BMI 25.1 (4.8) kg/m^2^; Weight loss: 33.1 (17.9) kg; - Physical activity: 2691 (2494) kcal/wk from physical activity; - Smoking: NR; - TEI: 1379 (573) kcal/d; - Habitual diet at baseline: Breakfast consumption 6.3 (1.8) d/wk; Meal frequency 4.7 (1.7) times/wk; Excluded from study or analysis: age <18y; did not maintain weight loss ≥30 lbs for ≥1 yr | Exposure:; Breakfast frequency (days/wk); Assessment methods and timing:; - FFQ used to assess frequency of breakfast consumption and number of daily meals; - At baseline; Outcomes and assessment methods:; - At baseline, 1y follow-up; - Weight was self-reported | [underlined: Weight regain at 1yr by breakfast consumption (days/wk)] r=−0.05, p=0.01 | Model adjustments:; - TEI: no; - Key confounders: none; - Other: none; Limitations:; - Did not account for key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, physical activity, smoking; - Exposure data only assessed at baseline leading to a concern that changes in exposure status occurred over 1yr f/u; - Selection into study maybe have been related to exposure and outcome; - Weight was self-reported; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; Community Foundation for Southeastern Michigan; NIH
Phelan, 2008^52^; PCS, National Weight Control Registry, U.S.; Analytic N=257 (post-holiday); 252 (1mo f/u); Study objective: To systematically compare the behaviors of successful weight losers vs normal weight losers before, during, and after the winter holiday season; Participant characteristics at baseline: adults with successful weight loss; - Age: ~46 (12)y; - Female: 75%; - Race and/or ethnicity: Caucasian: 96%; - Socioeconomic position: 73% ≥college education; - Anthropometry: BMI 25.5 (6.4) kg/m^2^ among successful weight losers; 21.8 (1.9) kg/m^2^ among normal weight participants; - Physical activity: NR; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: NR; Excluded from study or analysis: age <18y; among successful weight losers, those that did not maintain weight loss ≥30 lbs for ≥1 yr; among normal weight participants, those with BMI <18.5 or ≥25 kg/m^2^ | Exposure:; Breakfast frequency (days/wk); Assessment methods and timing:; - “Over the past month, on average how many days per week did you eat (breakfast, lunch, dinner, snacks, and dessert/sweets); - Before the holiday (Nov), and after the holiday (Jan); Outcomes and assessment methods:; - Before the holiday (Nov), after the holiday (Jan), and at 1mo follow-up (Feb); - Weight was self-reported | [underlined: Change in weight over 2mo (pre-holiday to post-holiday) based on pre-holiday breakfast frequency]; Data NR, p=NS; [underlined: Change in weight over 3mo (pre-holiday to 1mo after the holiday) based on pre-holiday breakfast frequency]; Data NR, p=NS | Model adjustments:; - TEI: no; - Key confounders: anthropometry at baseline; - Other: none; Limitations:; - Did not account for key confounders: sex, age, race and/or ethnicity, socioeconomic position, physical activity, smoking; - Selection into study maybe have been related to exposure and outcome; - High attrition rate; - Weight was self-reported; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; Funding NR
Sakurai, 2017^55^; PCS, Japan; Analytic N=4,430; Study objective: To investigate the relationship between frequency of skipping breakfast and annual changes in body mass index and waist circumference.; Participant characteristics at baseline: Japanese adults; - Age: Men, 39.2 (10.3)y; Women, 40.0 (9.8)y; - Female: 40%; - Race and/or ethnicity: NR, but likely majority Asian; - Socioeconomic position: All employed factory workers; - Anthropometry: BMI: Men, 23.3 (3.0) kg/m^2^ (26% overweight); Women, 21.9 (3.6) kg/m^2^ (15% overweight); - Physical activity: Habitual exercise: Men, ~48%; Women ~35%; - Smoking: Men: 38% current, 19% former, 43% never; Women: 7% current, 4% former, 89% never; - TEI: Men, ~2000 kcal/d; Women ~1700 kcal/d; - Habitual diet at baseline: Eat breakfast daily: 68% men, 74% women; Skip breakfast daily: 11% men, 6% women; Excluded from study or analysis: history of cancer at baseline; energy intake <500 or >5000 kcal/d; those that did not participate in consecutive annual follow-up health exams | Exposure:; Skipping breakfast (0, 1–3, 4–6, and 7 times/wk); Assessment methods and timing:; - "How many times do you skip breakfast in a week?" with 8 response categories ranging from ‘0 (eat breakfast everyday)’ to ‘7 (never eat breakfast)’.; - At baseline; Outcomes and assessment methods:; - Baseline, and annually for 5y; - Height, weight, and waist circumference (WC) were measured by staff at each health examination. BMI was calculated from height and weight. | [underlined: Difference in annual changes in WC (cm)], β; Men; 0 times/wk: REF; 1–3 times/wk: 0.042, p=0.439; 4–6 times/wk: 0.161, p=0.055; 7 times/wk: 0.248, p<0.001; Women; 0 times/wk: REF; 1–3 times/wk: −0.062, p=0.394; 4–6 times/wk: 0.067, p=0.607; 7 times/wk: −0.015, p=0.883; [underlined: Difference in annual changes in BMI (kg/m^2^)], β; Men; 0 times/wk: REF; 1–3 times/wk: 0.010, p=0.560; 4–6 times/wk: 0.061, p=0.025; 7 times/wk: 0.046, p=0.022; Women; 0 times/wk: REF; 1–3 times/wk: −0.012, p=0.547; 4–6 times/wk: 0.010, p=0.763; 7 times/wk: 0.001, p=0.970 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, anthropometry at baseline, physical activity, smoking; - Other: alcohol consumption; medical treatment for hypertension, hyperlipidemia, and diabetes mellitus at baseline; Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position; - Exposure data only assessed at baseline leading to a concern that changes in exposure status occurred over 5y f/u; - No information on non-completers; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; Funding:; Cancer Research UK; Medical Research Council; Stroke Association; British Heart Foundation; United Kingdom Department of Health; Europe Against Cancer Program Commission of the European Union; Food Standards Agency; Wellcome Trust
Seki, 2021^57^; RCS, Japan Medical Data Center Co., Ltd. - Specific Health Checkup Database, Japan; Analytic N=123,182; Study objective: To evaluate various eating and drinking habits and the risk of obesity using a large-scale health check-up database; Participant characteristics at baseline: healthy Japanese adults; - Age: Median 45y (IQR: 40–51y); - Female: 37%; - Race and/or ethnicity: NR, but likely majority Asian; - Socioeconomic position: All employed (mainly for large-scale companies); - Anthropometry: Median BMI 23.1 kg/m^2^; - Physical activity: 21% exercise ≥30min on ≥2d/wk; - Smoking: 29% current; - TEI: NR; - Habitual diet at baseline: 17% skip breakfast; 14% snack late at night; Excluded from study or analysis: aged <19y; missing baseline data; history of heart disease, stroke or kidney disease; BMI ≥25 kg/m^2^ or WC ≥85 cm for men and ≥90cm for women at baseline; did not receive a health exam at 5y follow-up | Exposure:; Skipping breakfast (yes/no); Assessment methods and timing:; - Questionnaire on eating and drinking habits, including: "I do not have breakfast at least 3 times a week: yes/no"; - At baseline; Outcomes and assessment methods:; - At baseline, 5y follow-up; - Height, weight, and waist circumference (WC) were measured at annual health exam; height and weight were used to calculate BMI. Obesity was defined as BMI ≥25 kg/m^2^ based on criteria determined by Japan Society for the Study of Obesity. Abdominal obesity defined as WC≥85cm for men and WC≥90cm for women. | [underlined: Abdominal obesity], OR (99% CI); Not skipping breakfast: REF; Skipping breakfast: 1.21 (1.13, 1.30) p<0.001; [underlined: Change in WC over 5y follow-up (cm) by skipping breakfast], β (SE); 0.026 (0.17, 0.34), p<0.001; [underlined: Obesity (BMI≥25 kg/m^2^)], OR (99% CI); Not skipping breakfast: REF; Skipping breakfast: 1.21 (1.10, 1.34) p<0.001; [underlined: Change in BMI over 5y follow-up (kg/m^2^) by skipping breakfast], β (SE); 0.07 (0.04, 0.09), p<0.001 | Model adjustments:; - TEI: no; - Key confounders: sex, age, anthropometry at baseline, physical activity, smoking; - Other: insufficient sleep; measured laboratory values (systolic BP, diastolic BP, LDL, HDL, TAG, AST, ALT, γ-glutamyl transpeptidase); weight gain ≥10kg from 20 years; weight gain ≥3kg in preceding year; drug use for hypertension, dyslipidemia, and diabetes; calendar year at baseline; frequency of drinking; amount of alcohol; eating speed; Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position; - Exposure data only assessed at baseline leading to a concern that changes in exposure status occurred over 5y f/u; - No information on non-completers; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; Suntory Beverage & Food Ltd; Japan Agency for Medical Research and Development
Smith, 2017^61^; PCS, Childhood Determinants of Adult Health (CDAH) study, Australia; Analytic N=1,155; Study objective: To examine whether meeting simple guidelines of ‘eat breakfast’, ‘limit takeaway and fast food to once per week’, ‘watch television less than 2 h per day’ and ‘take at least 10,000 steps per day’, was associated with 5-year weight gain among young adults.; Participant characteristics at baseline: young adults (26–36y); - Age: 31 (2)y; - Female: 57%; - Race and/or ethnicity: NR; - Socioeconomic position: University education: 43% men, 53% women; Vocational education: 35% men, 23% women; School only: 22% men, 24% women; Married: 68% men, 72% women; - Anthropometry: Overweight: 43% men, 24% women; Obesity: 14% men, 12% women; - Physical activity: ≥10,000 steps/d: ~34%; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: Eat breakfast: 71% men, 79% women; Excluded from study or analysis: pregnant at baseline or follow-up; missing data on all 4 behavior variables (breakfast, takeaway food, television viewing, 10k steps per day); missing data on weight; missing data on any covariates. | Exposure:; Eating breakfast between 6–9am.; Participants were classified according to whether they met the 2010 Dietary Guidelines for Americans recommendation to eat breakfast: consistently met at baseline and follow-up (reference group); not met at baseline but met at follow-up; met at baseline but not met at follow-up; consistently not met at baseline and follow-up.; Assessment methods and timing:; - Participants were asked to recall what/if they ate the previous day during specific time intervals. The response options were: no, a snack, a small meal, or a large meal. Skipping breakfast was defined as not eating a snack, small meal, or large meal between 6–9am.; - At baseline (2004–2006), 5y follow-up (2009–2011); Outcomes and assessment methods:; - At baseline, 5y follow-up; - Weight was measured by study staff or self-reported (for 11 participants at baseline who were unable to attend a study clinic and all participants at follow-up) | [underlined: Weight change over 5y (kg)], β (95% CI); Data NR (figure only); Consistently ate breakfast at baseline and follow-up: REF; Did not eat breakfast at baseline, but ate breakfast at follow-up: p=NS; Ate breakfast at baseline, but not at follow-up: greater weight gain, p<0.05; Consistently did not eat breakfast at baseline and follow-up: greater weight gain, p<0.05 | Model adjustments:; - TEI: no; - Key confounders: sex, age, socioeconomic position, anthropometry at baseline, smoking; - Other: day that meal patterns chart was completed at baseline and follow-up (weekend or weekday); Limitations:; - Did not account for key confounders: race and/or ethnicity, physical activity; - Exposure assessment method not validated; - Selection into study maybe have been related to exposure and outcome; - Missing data; - Weight was self-reported; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; National Health and Medical Research Council; National Heart Foundation; Tasmanian Community Fund; Veolia Environmental Services
Suka, 2020^62^; PCS, Japan; Analytic N=60,143; Study objective: To examine age-dependent trends in weight and lifestyle changes in Japanese workers.; Participant characteristics at baseline: Japanese adults (20–59y); - Age: 23% aged 20–29y; 27% aged 30–39y; 28% aged 40–49y; 22% aged 50–59y; - Female: 38%; - Race and/or ethnicity: NR, but likely majority Asian; - Socioeconomic position: All currently employed; majority were office workers; - Anthropometry: BMI: males ~23 kg/m^2^, females ~21 kg/m^2^; - Physical activity: Exercise <2x/wk: 72% males; 84% females; - Smoking: Males: 32% current; Females: 8% current; - TEI: NR; - Habitual diet at baseline: Skips breakfast: 32% males; 23% females; Excluded from study or analysis: pregnant participants; those who did not undergo health examination at 2yr follow-up for unknown reasons | Exposure:; Skipping breakfast >3 days/wk (yes vs no) Change in skipping breakfast behavior from baseline was coded as improved ( −1), worsened (1), and maintained (0).; Assessment methods and timing:; - "Do you skip breakfast more than three times a week? (Yes/No)"; - At baseline, 2y follow-up; Outcomes and assessment methods:; - At baseline, 2y follow-up; - Weight measured during annual health exam | [underlined: Weight gain from baseline to 2y (kg) by change in skipping breakfast behavior from baseline to 2y], β (SE); Males; New employees (20–24y): −0.37 (0.27), p=0.172; Existing employees (20–24y): −0.24 (0.17), p=0.150; Existing employees (25–29y): 0.13 (0.12), p=0.280; Existing employees (30–34y): −0.04 (0.12), p=0.714; Existing employees (35–39y): −0.15 (0.13), p=0.249; Existing employees (40–44y): −0.01 (0.13), p=0.954; Existing employees (45–49y): 0.15 (0.13), p=0.264; Existing employees (50–54y): −0.21 (0.15), p=0.174; Existing employees (55–59y): −0.11 (0.17), p=0.529; Females; New employees (20–24y): −0.21 (0.16), p=0.202; Existing employees (20–24y): −0.05 (0.13), p=0.700; Existing employees (25–29y): −0.19 (0.10), p=0.057; Existing employees (30–34y): 0.17 (0.13), p=0.173; Existing employees (35–39y): −0.08 (0.17), p=0.651; Existing employees (40–44y): −0.18 (0.17), p=0.300; Existing employees (45–49y): 0.17 (0.18), p=0.359; Existing employees (50–54y): −0.18 (0.18), p=0.339; Existing employees (55–59y): −0.37 (0.19), p=0.048; Consistent findings when breakfast skipping was analyzed using dummy variables (improved/worsened/maintained since baseline); [underlined: >2kg weight gain from baseline to 2y by change in skipping breakfast behavior from baseline to 2y], OR (95% CI); Males; New employees (20–24y): 0.97 (0.72, 1.29); Existing employees (20–24y): 0.90 (0.75, 1.09); Existing employees (25–29y): 0.98 (0.85, 1.12); Existing employees (30–34y): 0.84 (0.72, 0.97); Existing employees (35–39y): 0.89 (0.75, 1.06); Existing employees (40–44y): 0.91 (0.76, 1.09); Existing employees (45–49y): 0.95 (0.79, 1.15); Existing employees (50–54y): 0.93 (0.73, 1.18); Existing employees (55–59y): 0.90 (0.66, 1.22); Females; New employees (20–24y): 1.19 (0.90, 1.57); Existing employees (20–24y): 0.81 (0.64, 1.01); Existing employees (25–29y): 0.89 (0.75, 1.06); Existing employees (30–34y): 1.11 (0.90, 1.38); Existing employees (35–39y): 0.93 (0.72, 1.21); Existing employees (40–44y): 1.10 (0.83, 1.47); Existing employees (45–49y): 0.95 (0.68, 1.35); Existing employees (50–54y): 0.73 (0.50, 1.05); Existing employees (55–59y): 0.89 (0.56, 1.40) | Model adjustments:; - TEI: no; - Key confounders: sex, age, anthropometry at baseline; - Other:; Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position, physical activity, smoking; - Exposure assessment method not validated; - High attrition rate/missing data; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; No funding received
Tokumaru, 2020^65^; RCS, Japan; Analytic N=26,764; Study objective: To investigate the association between unhealthy dietary habits and proteinuria onset, which is a key prognostic factor of chronic kidney disease; Participant characteristics at baseline: Japanese adults; - Age: 68 (9)y; - Female: 56%; - Race and/or ethnicity: NR, but likely majority Asian; - Socioeconomic position: NR; - Anthropometry: BMI 22.8 (3.1) kg/m^2^; - Physical activity: NR; - Smoking: 14% current; - TEI: NR; - Habitual diet at baseline: 9% skip breakfast; 16% eat late evening snack; Excluded from study or analysis: <40y; glomerular filtration rate <60 mL/min/1.73 m^2^; follow-up period <1 year; baseline urinary protein dipstick result of ≥1+; missing data on status of dietary habits or other covariates | Exposure:; Skipping breakfast ≥3 times/wk (yes/no); Assessment methods and timing:; - Questionnaire on unhealthy dietary habits, including skipping breakfast and late evening snacking.; - At baseline; Outcomes and assessment methods:; - At baseline, 5y follow-up; - Height, weight, and waist circumference were measured during the health exam. Weight and height were used to calculate BMI, and waist circumference and height were used to calculate waist-to-height ratio. | [underlined: Change in waist-to-height ratio (cm/cm) over 5y follow-up], Mean (95% CI); Data NR (figure only), p=0.825; [underlined: Change in BMI (kg/m^2^) over 5y follow-up], Mean (95% CI); Data NR (figure only), Skipping breakfast < No skipping: p=0.049 | Model adjustments:; - TEI: no; - Key confounders: sex, age, anthropometry at baseline, smoking; - Other: systolic blood pressure; estimated glomerular filtration rate; hemoglobin; triglyceride; total cholesterol; HbA1c; serum uric acid; daily drinking; Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position, physical activity; - Exposure data only assessed at baseline leading to a concern that changes in exposure status occurred over 5y f/u; - No information on non-completers; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; No external funding
van der Heijden, 2007^67^; PCS, Health Professionals Follow-up Study, U.S.; Analytic N=20,064; Study objective: To investigate the association between breakfast consumption and weight gain in an adult male population over a 10-year period.; Participant characteristics at baseline: middle-age and older men; - Age: ~57y; - Female: 0%; - Race and/or ethnicity: NR; - Socioeconomic position: All health professionals; ~77% work full-time; - Anthropometry: BMI ~25.6 kg/m^2^; - Physical activity: ~38 MET hr/wk; ~21% any weight training; - Smoking: ~6% current; - TEI: NR; - Habitual diet at baseline: 17% skip breakfast; Excluded from study or analysis: missing values for breakfast skipping or BMI at baseline; implausible energy intakes (>4200 or <800 kcal/d); >70 blank items on FFQ; history of diabetes, CVD, or cancer (except non-melanoma skin cancer) at baseline; died during follow-up or missing values for BMI at follow-up | Exposure:; Breakfast consumers vs Breakfast non-consumers; Assessment methods and timing:; - “Please indicate the times of day that you usually eat.” The participants could mark all of the predefined answer categories that applied (before breakfast, breakfast, between breakfast and lunch, lunch, between lunch and dinner, dinner, between dinner and bedtime, and after going to bed).; - At baseline (1992); Outcomes and assessment methods:; - At baseline (1992), biennially until 2002; - Weight was self-reported. Substantial weight gain was defined as weight gain of ≥5 kg. | [underlined: 5 kg weight gain over 10y follow-up], HR (95% CI); All men; Breakfast non-consumers (n=1312): REF; Breakfast consumers (n=4545): 0.87 (0.82, 0.93); Participants with baseline BMI <25 kg/m^2^:; Breakfast non-consumers: REF; Breakfast consumers: 0.78 (0.70, 0.87); Participants with baseline BMI ≥25 kg/m^2^:; Breakfast non-consumers: REF; Breakfast consumers: 0.92 (0.85, 1.00) | Model adjustments:; - TEI: no; - Key confounders: sex, age, socioeconomic position, anthropometry at baseline, physical activity, smoking; - Other: alcohol intake; Limitations:; - Did not account for key confounders: race and/or ethnicity; - Exposure data only assessed at baseline leading to a concern that changes in exposure status occurred over 10y f/u; - High attrition rate; - Weight was self-reported; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; NIH
Yamamoto, 2021^74^; RCS, Japan; Analytic N=17,573 (males); 8860 (females); Study objective: To assess the clinical impact of skipping breakfast, lunch, and dinner on weight gain and overweight/obesity in university students within their 6-year college life; Participant characteristics at baseline: Japanese university students; - Age: Males: 65% age 18y, 32% age 19y, 3% age ≥20y; Females: 74% age 18y, 23% age 19y, 3% age ≥20; - Female: 34%; - Race and/or ethnicity: NR, but likely majority Asian; - Socioeconomic position: All university students; - Anthropometry: BMI: males 21.6 (2.9) kg/m^2^; females 20.5 (2.4) kg/m^2^; - Physical activity: NR; - Smoking: <1% current; - TEI: NR; - Habitual diet at baseline: Eat breakfast daily: 81% males, 88% females; Skips breakfast often: 6% males, 3% females; Eat lunch daily: 94% males, 95% females; Eat dinner daily: 98% males, 96% females; Excluded from study or analysis: <18y; missing baseline data; missing body weight data during 6y observation period | Exposure:; Breakfast (eating every day, skipping occasionally, or skipping often/usually); Assessment methods and timing:; - "How often did you have breakfast/lunch/dinner over the past year?"; responses were "eating almost every day", "skipping occasionally", "skipping often", and "usually skipping".; - At baseline; Outcomes and assessment methods:; - At baseline, and annually for 6y; - Weight measured during annual health exam. Incidence of weight gain ≥10% was measured in all students and incidence of overweight/obesity (BMI ≥25 kg/m^2^) was measured in students with a BMI <25 kg/m^2^. | [underlined: Weight gain ≥10%], IRR (95% CI); Males; Eating breakfast every day: REF; Skipping breakfast occasionally: 0.97 (0.85, 1.11); Skipping often/usually: 1.18 (0.99, 1.40); Females; Eating breakfast every day: REF; Skipping breakfast occasionally: 0.98 (0.82, 1.17); Skipping often/usually: 0.84 (0.62, 1.13); [underlined: Overweight/obesity (BMI ≥25 kg/m^2^)], IRR (95% CI); Males; Eating breakfast every day: REF; Skipping breakfast occasionally: data NR (figure only), NS; Skipping often/usually: data NR (figure only), NS; Females; Eating breakfast every day: REF; Skipping breakfast occasionally: data NR (figure only), NS; Skipping often/usually: data NR (figure only), NS | Model adjustments:; - TEI: no; - Key confounders: sex, age, anthropometry at baseline, smoking; - Other: admission year; drinking status; sleep duration on weekdays; dinner time; breakfast, lunch, and dinner frequency (e.g., breakfast frequency was adjusted for lunch and dinner frequencies); Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position, physical activity; - Exposure data only assessed at baseline leading to a concern that changes in exposure status occurred over 6y f/u; - No information on non-completers; - No preregistered data analysis plan and concerns related to selective reporting were present; - Water/Beverages were not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; No external funding
Zhang, 2017^75^; PCS, Secondary analysis of an RCT comparing AHA diet to high-fiber diet, U.S.; Analytic N=178; Study objective: To examine the association between breakfast skipping and body weight, nutrient intake, and metabolic parameters in participants with metabolic syndrome; Participant characteristics at baseline: adults with MetS; - Age: 52.2y; - Female: 73%; - Race and/or ethnicity: White: 88%; Other: 12%; - Socioeconomic position: Education: 75% Bachelor's degree or less; 25% Graduate/professional; Household income: 27% ≤$50k, 50% ≥$50,001, 23% unclear; 79% employed full-time or part-time; - Anthropometry: 48% BMI 30–34.9 and 52% BMI 35–40 kg/m^2^; - Physical activity: Mean duration of total physical activity: 235 min/wk in NB group vs 200 min/wk in Breakfast group, p=0.02; - Smoking: All nonsmokers; - TEI: Breakfast: 1984 kcal/d vs NB: 1816 kcal/d; p=0.05; - Habitual diet at baseline: 33% skipped breakfast, 33% ate breakfast daily; Excluded from study or analysis: age <21 and >70y; BMI <30 and >40 kg/m^2^; smokers; no diagnosis of MetS; clinically diagnosed diabetes or fasting blood sugar levels ≥126 mg/dL, an acute coronary event within last 6mo, pregnant or lactating, PCOS, intention to move out of the area within 1yr study period, current participation in a weight loss program, an eating disorder, bariatric surgery, elevated depression or suicidal ideation, or subjects following a low-carbohydrate, high fat dietary regimen. | Exposure: Breakfast vs No Breakfast (NB); Participants who reported eating breakfast at least once were considered breakfast eaters and those who did not consume any breakfast on the three dietary recall days were categorized as breakfast skippers. Breakfast included consumption of any food/beverage (excluding water) at the first eating episode no later than 10am.; Assessment methods and timing:; - Self-reported using three unannounced 24hr diet recalls; - At baseline; Outcomes and assessment methods:; - At baseline, 1yr follow-up; - Height, weight, and WC: measured by trained study staff; height and weight used to calculate BMI | [underlined: Change in WC (in) over 1yr], Mean (95% CI); NB: 0.5 (−0.5, 1.4); Breakfast: −0.2 (−0.8, 0.4) p=0.16; [underlined: Change in BMI (kg/m^2^) over 1yr], Mean (95% CI); NB: −1.0 (−3.7, 1.7); Breakfast: −1.6 (−3.2, −0.0) p=0.60; [underlined: Change in weight (lb) over 1yr], Mean (95% CI); NB: −6.6 ( −11.3, −1.9); Breakfast: −5.7 (−8.6, −2.9) p=0.68 | Model adjustments:; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, physical activity, smoking; - Other: group; Limitations:; - Did not account for key confounders: anthropometry; - Exposure assessment method not validated and exposure data only assessed at baseline leading to a concern that changes in exposure status occurred over 1yr f/u; - No information on non-completers; - No preregistered data analysis plan; Funding:; NHLBI; China Scholarship Council

a Abbreviations: ALT: alanine aminotransferase; AST: aspartate aminotransferase; AUD: Australian Dollar; β: beta coefficient; BMI: body mass index; BMIz: body mass index z-score; BP: blood pressure; CDC: Centers for Disease Control and Prevention; CI: confidence interval; cm: centimeter(s); d: day(s); DEXA: dual energy x-ray absorptiometry; FFQ: food frequency questionnaire; g: gram(s); GGT: gamma-glutamyl transferase; HbA1c: hemoglobin A1C; HOMA-IR: Homeostatic Model Assessment of Insulin Resistance; hr: hour(s); HR: hazard ratio; IOTF: International Obesity Task Force; IQR: interquartile range; kcal: kilocalorie(s); kg: kilogram(s); lb: pound(s); m: meter(s); MET: metabolic equivalent; min: minute(s); mm: millimeter(s); MVPA: moderate to vigorous physical activity; N/A: not applicable; NCC: nested case control study; NCI: National Cancer Institute; NHLBI: National Heart, Lung, and Blood Institute; NICHD; Eunice Kennedy Shriver National Institute of Child Health and Human Development; NIDDK: National Institute of Diabetes and Digestive and Kidney Diseases; NIH: National Institutes of Health; NISOC: nmol: nanomole; NR: not reported; NS: not significant; OR: odds ratio; PCS: prospective cohort study; Project EAT: Project Eating and Activity over Time; RCS: retrospective cohort study; REF: reference group; RMB: renminbi (Chinese yuan); RR: risk ratio; SD: standard deviation; SDS: standard deviation score; SE: standard error; SEP: socioeconomic position; SES: socioeconomic status; svg: serving(s); TAG: triacylglycerol; TEI: total energy intake; wk: week(s); x: time(s); y: year(s)

Table 22 Risk of bias for randomized controlled trials examining breakfast in adults and older adults and body composition and risk of obesity^a^

Article | Randomization | Deviations from intended interventions (per-protocol) | Missing outcome data | Outcome measurement | Selection of the reported result | Overall risk of bias
Dhurandhar, 2014^11^ | LOW | LOW | LOW | LOW | LOW | LOW
Leidy, 2015^37^ | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS

a Possible ratings of low, some concerns, or high determined using the "Cochrane Risk-of-bias 2.0" (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898. doi:10.1136/bmj.l4898. )

Table 23 Risk of bias for observational studies examining breakfast in adults and older adults and body composition and risk of obesity^b^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Bajerska, 2020^3^ | HIGH | HIGH | VERY HIGH | HIGH | VERY HIGH | LOW | LOW | VERY HIGH
Elahy, 2023^14^ | LOW* | SOME CONCERNS | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Goto, 2010^18^ | HIGH | HIGH | SOME CONCERNS | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Guinter, 2020^19^ | LOW* | HIGH | LOW | LOW | SOME CONCERNS | HIGH | SOME CONCERNS | HIGH
Kito, 2019^29^ | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | LOW | HIGH | LOW | SOME CONCERNS | HIGH
LaRose, 2019^32^ | VERY HIGH | SOME CONCERNS | LOW | SOME CONCERNS | HIGH | LOW | SOME CONCERNS | VERY HIGH
Larson, 2020^33^ | HIGH | LOW | LOW | LOW | SOME CONCERNS | HIGH | SOME CONCERNS | HIGH
Martinez, 2021^42^ | LOW* | SOME CONCERNS | LOW | LOW | HIGH | HIGH | HIGH | HIGH
Megson, 2017^43^ | HIGH | SOME CONCERNS | LOW | LOW | HIGH | LOW | HIGH | HIGH
Nishiura, 2010^48^ | VERY HIGH | VERY HIGH | LOW | LOW | HIGH | LOW | HIGH | VERY HIGH
Nooyens, 2005^49^ | SOME CONCERNS | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Odegaard, 2013^50^ | LOW* | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Phelan, 2006^53^ | VERY HIGH | SOME CONCERNS | HIGH | LOW | SOME CONCERNS | HIGH | SOME CONCERNS | VERY HIGH
Phelan, 2008^52^ | HIGH | SOME CONCERNS | LOW | LOW | HIGH | HIGH | SOME CONCERNS | HIGH
Sakurai, 2017^55^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Seki, 2021^57^ | SOME CONCERNS | HIGH | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Smith, 2017^61^ | HIGH | LOW | LOW | LOW | SOME CONCERNS | HIGH | SOME CONCERNS | HIGH
Suka, 2020^62^ | HIGH | HIGH | LOW | LOW | HIGH | LOW | HIGH | VERY HIGH
Tokumaru, 2020^65^ | HIGH | HIGH | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
van der Heijden, 2007^67^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | HIGH | SOME CONCERNS | HIGH
Yamamoto, 2021^74^ | HIGH | SOME CONCERNS | LOW | LOW | HIGH | LOW | VERY HIGH | VERY HIGH
Zhang, 2017^75^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH

b Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the "Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)" tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.

Table 24 Evidence examining the relationship between breakfast during pregnancy and gestational weight gain^a^

Study and Population Characteristics | Intervention, Comparator, and Outcome(s) | Results | Study Limitations
Dolin, 2020^12^; PCS, Secondary analysis of Starting Early Child Obesity Prevention Study RCT, U.S.; Analytic N=508; Study objective: To determine associations between sociodemographic characteristics, health behaviors, and psychosocial stressors and gestational weight gain in low-income Hispanic women; Participant characteristics at baseline: low-income Hispanic women during pregnancy; - Age: Mean NR; 63% <30y, 37% ≥30y; - Female: 100%; - Race and/or ethnicity: Hispanic: 100%; Country of birth: 19% US, 48% Mexico, 33% Other Latin Countries; 81% with Spanish as primary language; - Socioeconomic position: 87% received WIC; 36% received SNAP; 74% unemployed; - Anthropometry: Pre-pregnancy BMI: 35% normal, 34% overweight, 32% obesity; - Physical activity: 55% met physical activity recommendations prior to pregnancy; - Smoking: NR; - Parity: 37% nulliparous; - Diabetes: NR; - Hypertensive Disorders: NR; - TEI: NR; - Habitual diet at baseline: 81% eat breakfast every day; Excluded from study or analysis: did not self-identify as Hispanic; age <18y; complicated pregnancy; multiple pregnancy; significant medical or psychiatric illness, homelessness, and/or fetal anomalies; missing baseline data or information on GWG; unknown age at delivery; BMI <18.5 kg/m^2^ prior to pregnancy | Exposure:; Eats breakfast every day (yes/no); Assessment methods and timing:; - Women were asked whether they consumed breakfast on a daily basis (as part of a FFQ assessing intake during the previous 12mo); - During 3rd trimester; Outcomes and assessment methods:; - At delivery (gestational age 39.4 (1.3)wk); - Gestational weight gain (GWG) calculated by subtracting measured or self-reported initial prenatal weight (mean gestational age 7.8 (1.9)wk) from measured weight when admitted at delivery. Adequacy of GWG (inadequate, adequate, excessive) was determined using 2009 IOM recommendations. | [underlined: GWG based on eating breakfast every day], RR (95% CI); Inadequate: 0.47 (0.26, 0.83), p<0.05; Excessive: 0.65 (0.35, 1.18), p=NS; Total (unadjusted analysis): 0.06 ( −1.12, 1.23), p=NS | Model adjustments:; - TEI: no; - Key confounders: age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, physical activity, parity; - Other: dietary intake (dairy, vegetables, whole fruit, refined grains, protein); screen time; psychosocial stressors (depressive symptoms, financial difficulties, housing disrepair, food insecurity, neighborhood stress); Limitations:; - Did not account for key confounders: smoking, diabetes mellitus in the current pregnancy, hypertensive disorders in the current pregnancy; - Exposure assessment method not validated; Start of follow-up and exposure do not coincide; - No information on non-completers; - Outcomes were self-reported for some women; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; USDA; NICHD
Samano, 2022^56^; PCS, Mexico; Analytic N=530; Study objective: To analyze whether there is an association between dietary and nutrient intake and eating habits and GWG among pregnant adolescents and their offspring’s birth weight; Participant characteristics at baseline: pregnant adolescents aged 11–19y; - Age: 15.8 (1.3)y; - Female: 100%; - Race and/or ethnicity: NR but likely majority Hispanic; - Socioeconomic position: 75% elementary education; 89% school dropout; Mostly low or very low SES; 70% single; 30% cohabitating; 89% homemakers; - Anthropometry: NR; - Physical activity: NR; - Smoking: NR; - Parity: All primigravida (inclusion criteria); - Diabetes: NR but likely none since chronic disease was an exclusion criteria; - Hypertensive Disorders: NR but likely none since chronic disease was an exclusion criteria; - TEI: 2022 (657) kcal/d; - Habitual diet at baseline: 20% had ≤2 meals/d; 56% skipped meals >1x/wk; Excluded from study or analysis: multigravida or multiple pregnancy; chronic disease; drug addictions; vegans or vegetarians; those who had a newborn with congenital malformations or stillbirth | Exposure:; Eating breakfast (yes/no); Assessment methods and timing:; - Participants were asked about their number of meals and frequency of skipping meals (never, 1–3x/wk, 4–5x/wk); - At baseline ("during first visit", details NR); Outcomes and assessment methods:; - 1–2wk before delivery; - Gestational weight gain (GWG) calculated by subtracting self-reported initial pre-pregnancy weight from measured final gestational weight. Adequacy of GWG was based on IOM recommendations and was categorized as inadequate/insufficient (<90%), adequate (90 to <125%), and excessive (≥125%). | [underlined: GWG adequacy percentage], unadjusted Chi-square; Ate breakfast: 36.6% insufficient, 36.8% excessive; Skipped breakfast: 52% insufficient, 32% excessive; p=0.263 | Model adjustments:; - TEI: no; - Key confounders: age, socioeconomic position, anthropometry at baseline, parity, diabetes mellitus in the current pregnancy, hypertensive disorders in the current pregnancy; - Other: gynecological age, antenatal care; Limitations:; - Did not account for key confounders: race and/or ethnicity, physical activity; - Exposure assessment method not validated; - Timing of exposure measurement not described; - No information on non-completers; - Outcomes were based on self-reported pre-pregnancy weight; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; Instituto Nacional de Perinatología; CONACyT

a Abbreviations: CI: confidence interval; d: day(s); FFQ: food frequency questionnaire; GWG: gestational weight gain; IOM: Institute of Medicine; NR: not reported; NS: not significant; PCS: prospective cohort study; REF: reference group; RR: risk ratio; SNAP: Supplemental Nutrition Assistance Program; TEI: total energy intake; WIC: Special Supplemental Nutrition Program for Women, Infants and Children; wk: week(s); y: year(s)

Table 25 Risk of bias for observational studies examining breakfast in individuals during pregnancy and gestational weight gain^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Dolin, 2020^12^ | HIGH | HIGH | SOME CONCERNS | LOW | HIGH | HIGH | SOME CONCERNS | HIGH
Samano, 2022^56^ | HIGH | HIGH | SOME CONCERNS | LOW | HIGH | HIGH | SOME CONCERNS | VERY HIGH

a Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the "Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)" tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. )

Table 26 Evidence examining the relationship between snacking in children and adolescents and growth, body composition, and risk of obesity^a^

Study and Population Characteristics | Intervention, Comparator, and Outcome(s) | Results | Study Limitations
Choi, 2022^78^; PCS, Korean National Health Insurance Service (NHIS), South Korea; Analytic N=26,047; Study objective: To identify the risk factors of obesity in 5yo children; Participant characteristics at baseline: children; - Age: 3y; - Female: 49%; - Race and/or ethnicity: NR but likely majority Asian; - Socioeconomic position: Mother's income level: 49% High, 32% Middle, 19% Low; - Anthropometry: NR; - Physical activity: 74% engaged in "sweat-inducing" physical activities ≥1 hr/d; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: 89% eat 3 meals/day; 69% eat 2 snacks/day and 24% eat ≥3 snacks/day; Excluded from study or analysis: no confirmed BMI, availability of an identical mother-child health insurance number, or availability of mother's BMI and income levels; mother's delivery and child's birth were not in the same year; missing availability of children's fourth (at 3y) health check-up records and birth data | Exposure:; Number of snacks per day (1, 2, ≥3); Assessment methods and timing:; - Nutrition questionnaire at health screening on number of meals and snacks per day; - At baseline (age 3y); Outcomes and assessment methods:; - At baseline (age 3y), and 2y follow-up; - Weight and height were measured by trained personnel and used to calculate BMI. Obesity was defined as BMI ≥ sex- and age-specific 95th% according to 2007 Korean National Growth Charts. | [underlined: Obesity at 5y based on snacking frequency at 3y], OR (95% CI); 1x/d: REF; 2x/d: 1.00 (0.77, 1.30), p=0.989; ≥3x/d: 0.85 (0.64, 1.12), p=0.244 | Model adjustments:; - TEI: no; - Key confounders: sex, age, socioeconomic position, physical activity; - Other: birth weight; developmental screening; mother's BMI; infant feeding mode; various measures of dietary behavior and intake; TV; Limitations:; - Did not account for key confounders: race and/or ethnicity, anthropometry at baseline; - Exposure data only assessed at baseline leading to a concern that changes in exposure status occurred over 2y f/u; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; No external funding
Elgar, 2005^15^; PCS, Health Behaviour of School-aged Children Study, UK; Analytic N=355; Study objective: To study the prevalence and stability of overweight and obesity in a cohort of adolescents, and the effects of sedentary behavior and physical activity on changes in body mass.; Participant characteristics at baseline: adolescents 11–14y; - Age: 12.3 (6.3)y; - Female: 55%; - Race and/or ethnicity: NR; - Socioeconomic position: NR; - Anthropometry: 20% with overweight/obesity; - Physical activity: NR; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: NR; Excluded from study or analysis: missing data at baseline or follow-up; in private or special needs schools; incarcerated | Exposure:; Snacks (number consumed per day); Assessment methods and timing:; - Questionnaire with items related to dieting and meal skipping; - At baseline; Outcomes and assessment methods:; - At baseline, 4y follow-up; - Weight and height were measured by study personnel and used to calculate BMI. | [underlined: BMI (kg/m^2^) at 4y follow up], β (SE); Snacks per day: −0.08 (0.11), p=NS | Model adjustments:; - TEI: no; - Key confounders: sex, age, socioeconomic position, anthropometry at baseline, physical activity; - Other: number of other meals skipped; number of hours per week spent watching television or videos, or playing computer games; Limitations:; - Did not account for key confounders: race and/or ethnicity; - Exposure was only measured at baseline and subject to measurement error; - Did not provide evidence as to whether the result was unbiased due to missing data; - No preregistered data analysis plan; - Water was not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; Welsh Assembly Government
Francis, 2003^79^; PCS, U.S.; Analytic N=173; Study objective: To examine whether television viewing provides a context for patterns of snacking fostering overweight in young girls from overweight and non-overweight families; Participant characteristics at baseline: young girls; - Age: 5.4 (0.3)y; - Female: 100%; - Race and/or ethnicity: All White; - Socioeconomic position: "Well-educated"; Predominantly middle-class; - Anthropometry: BMI ~16 (1.6) kg/m^2^; - Physical activity: scale of 1–5: 2.8 (0.4); - Smoking: NR; - TEI: NR; - Habitual diet at baseline: Snacking ~1.8 (0.7) times/d; Excluded from study or analysis: not living with both biological parents; severe food allergies or chronic medical problems affecting food intake; dietary restrictions involving animal products; and extreme outliers | Exposure:; Snacking frequency (times/d); Food items consumed between 2 consecutive meals were defined as one snacking occasion.; Assessment methods and timing:; - Three 24hr recalls (two weekdays and one weekend) was used to collect data on snacking.; - At age 5, 7, and 9y; Outcomes and assessment methods:; - At age 5, 7, and 9y; - Weight and height were measured by trained personnel and used to calculate BMI. BMI cut-offs were based on international data and correspond to the 85th and 95th percentile for children for overweight and obesity. Used cut-offs for the half year (5.5, 7.5, 9.5) to account for the array of birth dates. | [underlined: Change in BMI (kg/m^2^) from age 5–9y by snacking frequency], Correlation; Both parents with non-overweight (n=101): −0.03, p=NS; One or both parents with overweight (n=72): −0.05, p=NS | Model adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, anthropometry at baseline; - Other: parental weight status; Limitations:; - Did not account for key confounders: socioeconomic position, physical activity; - No evidence whether the result was biased due to missing data; - No preregistered data analysis plan; - Unclear if water/Beverages were accounted for in exposure assessment; - Did not adjust for TEI; Funding:; NIH
Lee, 2018^35^; PCS, South Korea; Analytic N=93; Study objective: To investigate behavioral factors that contribute to the development of obesity among overweight children; Participant characteristics at baseline: elementary and middle school students aged 9–13y; - Age: ~10–11 (1.4)y; - Female: 24%; - Race and/or ethnicity: NR, likely majority Asian; - Socioeconomic position: NR; - Anthropometry: BMI ~23 (1) kg/m^2^; ~23 (3)% body fat; - Physical activity: Physical fitness score: ~36; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: 36% ate frequent or night snack; Excluded from study or analysis: missing data on one or more measures | Exposure:; Frequent night snacking (yes/no); Assessment methods and timing:; - Children were asked about night snacking; - At baseline; Outcomes and assessment methods:; - At baseline, 1y follow-up; - Weight, height, waist circumference, and body fat (bioimpedance) were measured by study personnel. Weight and height were used to calculate BMI. Overweight (≥85th percentile) and obesity (≥95th percentile) were based on Korean CDC standard growth charts. | [underlined: Weight status (% normal weight, overweight, obesity) at 1y follow-up], unadjusted analysis No frequent night snacking: 65.5, 52.5, 78.3; Frequent night snacking: 34.5, 47.5, 21.7 p=0.425 | Model adjustments:; - TEI: no; - Key confounders: sex, age, anthropometry at baseline; - Other:; Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position, physical activity; - Exposure data only assessed at baseline leading to a concern that changes in exposure status occurred over 1y f/u; - Snacking exposure not well defined and subject to measurement error; - No evidence whether the result was biased due to missing data; - No preregistered data analysis plan; - Did not report results for some outcomes measured; - Water was not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; National Research Foundation for Korea
Lee, 2012^81^; PCS, Obesity and Metabolic Disorders Cohort in Childhood, South Korea; Analytic N=1504 (474 first graders, 1030 fourth graders); Study objective: To assess risk factors associated with children's body mass index and their changes over a 2-year period; Participant characteristics at baseline:; Korean 1st and 4th grade children; - Age: 7.3(0.3)y and 10.0(0.4)y; - Female: 51%; - Race and/or ethnicity: NR but majority likely Asian; - Socioeconomic position: 33% ≤12y maternal education; 23% ≤12y paternal education; 70% >3 million Korean Wan; 89% with two parent household; - Anthropometry: BMI 16.0 (2.3) kg/m^2^ in first graders, 18.1 (3.0) kg/m^2^ in fourth graders; - Physical activity: Exercise ≥5 days/wk: 17% first graders, 13% fourth graders; - Smoking: NR; - TEI: 1800 (300) kcal/d in first graders, 1700 (400) in fourth graders; - Habitual diet at baseline: 23% snacking; Excluded from study or analysis: missing data | Exposure:; Snacking (yes/no); Assessment methods and timing:; - Three 24hr recalls (two weekdays and one weekend) was used to collect data on frequency of skipping meals and snack intake; - At baseline; Outcomes and assessment methods:; - At baseline, 2y follow-up; - Height and weight were measured by trained personnel and used to calculate BMI. BMI percentile was based on age and sex specific 2007 growth chart for Korean children. | [underlined: Change in BMI (kg/m^2^) during 2y follow-up], β (95% CI) 1st graders; No snacking: REF; Snacking: 0.189 (−0.098, 0.476) p=0.196; 4th graders; No snacking: REF; Snacking: 0.278 (0.066, 0.490) p=0.010 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, socioeconomic position, anthropometry at baseline, physical activity; - Other: screen time; sleep duration; parental BMI; sexual maturation; Limitations:; - Did not account for key confounders: race and/or ethnicity; - Exposure data only assessed at baseline leading to a concern that changes in exposure status occurred over 2y f/u; - No information on non-completers; - No preregistered data analysis plan; - Unclear if water/beverages were accounted for in exposure assessment; Funding:; NR
Narla, 2019^45^; PCS, NHLBI Growth and Health Study, U.S.; Analytic N=2,024; Study objective: To rank the importance of potentially modifiable psychosocial, dietary, behavioral and environmental risk and protective factors for female adolescent obesity; Participant characteristics at baseline: Black and White adolescent females; - Age: 10y; - Female: 100%; - Race and/or ethnicity: White: 48%; Black: 52%; - Socioeconomic position: Parental education: 24%<high school, 36% college graduate; 40% post-graduate; Household income 16%≤$9,999; 13.5% $10k–19,999; 29% $20k-39,999; 36% ≥$40k; 5.5% not available; - Anthropometry: BMI 18.5 kg/m^2^; - Physical activity: NR; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: NR; Excluded from study or analysis: missing outcome data | Exposure:; Morning snack (yes/no); Afternoon snack (yes/no); Evening snack (yes/no); Assessment methods and timing:; - 3d food diary (included 1 weekend day); - At baseline (age 9–10y); Outcomes and assessment methods:; - At baseline, and 10y follow-up (age 19y); - Body fat percentage was measured by sum of skinfolds measured by study personnel | [underlined: Body fat % at 10y follow-up by baseline snacking], β (SE); Morning snack: Data not reported; p=NS Afternoon snack: −4.64 (1.03), p=0.00; Evening snack: −2.23 (0.71), p=0.01 | Model adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline; - Other: parent education; Limitations:; - Did not account for key confounders: physical activity; - Exposure data only assessed at baseline leading to a concern that changes in exposure status occurred over f/u; - Exposure were not well defined and subject to measurement error; - No preregistered data analysis plan; - Water/beverages were not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; Stanford Medical Scholars Program; NIA
Ritchie, 2012^84^; PCS, NHLBI Growth and Health Study, U.S.; Analytic N=2,146; Study objective: To assess the prospective relation of an objective measure of eating frequency with adiposity in girls from ages 9–10 to 19–20y.; Participant characteristics at baseline: Black and White adolescent females; - Age: 9–10y; - Female: 100%; - Race and/or ethnicity: White: 49%; Black: 51%; - Socioeconomic position: 8.59 (3.43) maximum years of parental education by either parent; - Anthropometry: BMI 18.6 (3.8) kg/m^2^; - Physical activity: "sometimes" physically active; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: Snacks 2.4 (2.1) times/d; Excluded from study or analysis: not age within 2wk of 9–10y, black or white, living with parents or guardians with racial concordance, and parent or guardian providing information on the demographic characteristics; not missing data on any control variables | Exposure:; Snacking frequency (0–1, 1.1–2, 2.1–3, >3 times/d); Assessment methods and timing:; - 3d diet record; - At baseline (averaged over 2 visits at ages 9–11y); Outcomes and assessment methods:; - At baseline, 10y follow-up; - Height, weight, and waist circumference (WC) were measured by trained examiners. BMI was calculated from height and weight. | [underlined: Change in WC (cm) over 10y based on baseline snacking frequency], Mean (SE); ALL; 0–1x/d: 12.04 (0.66); 1.1–2x/d: 11.81 (0.64); 2.1–3x/d: 11.79 (0.69); >3x/d: 10.52 (0.67) p=NS; BLACK; Lower snack frequency associated with greater increases in WC, p=0.005; WHITE; Lower snack frequency associated with greater increases in WC, p=0.030; [underlined: Change in BMI (kg/m^2^) over 10y based on baseline snacking frequency], Mean (SE); ALL; 0–1x/d: 7.40 (0.26); 1.1–2x/d: 7.45 (0.26); 2.1–3x/d: 7.25 (0.29); >3x/d: 6.77 (0.28) p=NS; BLACK; Lower snack frequency associated with greater increases in BMI, p=0.022; WHITE; Lower snack frequency associated with greater increases in BMI, p=0.023 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, physical activity; - Other: dieting for weight loss, TV/video viewing; Limitations:; - Exposure data only assessed at baseline leading to a concern that changes in exposure status occurred over 10y f/u; - No information on non-completers; - No preregistered data analysis plan; - Beverages was not accounted for in exposure assessment; Funding:; USDA; NIH

a Abbreviations: ALT: alanine aminotransferase; AST: aspartate aminotransferase; AUD: Australian Dollar; β: beta coefficient; BMI: body mass index; BMIz: body mass index z-score; BP: blood pressure; CDC: Centers for Disease Control and Prevention; CI: confidence interval; cm: centimeter(s); d: day(s); DEXA: dual energy x-ray absorptiometry; FFQ: food frequency questionnaire; g: gram(s); GGT: gamma-glutamyl transferase; HbA1c: hemoglobin A1C; HOMA-IR: Homeostatic Model Assessment of Insulin Resistance; hr: hour(s); HR: hazard ratio; IOTF: International Obesity Task Force; IQR: interquartile range; kcal: kilocalorie(s); kg: kilogram(s); lb: pound(s); m: meter(s); MET: metabolic equivalent; min: minute(s); mm: millimeter(s); MVPA: moderate to vigorous physical activity; N/A: not applicable; NCC: nested case control study; NCI: National Cancer Institute; NHLBI: National Heart, Lung, and Blood Institute; NICHD; Eunice Kennedy Shriver National Institute of Child Health and Human Development; NIDDK: National Institute of Diabetes and Digestive and Kidney Diseases; NIH: National Institutes of Health; NISOC: nmol: nanomole; NR: not reported; NS: not significant; OR: odds ratio; PCS: prospective cohort study; Project EAT: Project Eating and Activity over Time; RCS: retrospective cohort study; REF: reference group; RMB: renminbi (Chinese yuan); RR: risk ratio; SD: standard deviation; SDS: standard deviation score; SE: standard error; SEP: socioeconomic position; SES: socioeconomic status; svg: serving(s); TAG: triacylglycerol; TEI: total energy intake; wk: week(s); x: time(s); y: year(s)

Table 27 Risk of bias for observational studies examining snacking in children and adolescents and growth, body composition, and risk of obesity^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Choi, 2022^78^ | HIGH | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Elgar, 2005^15^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Francis, 2003^79^ | HIGH | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Lee, 2012^81^ | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Lee, 2018^35^ | HIGH | HIGH | SOME CONCERNS | LOW | HIGH | LOW | HIGH | VERY HIGH
Narla, 2019^45^ | SOME CONCERNS | HIGH | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Ritchie, 2012^84^ | LOW* | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH

a Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the "Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)" tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602 .) *Low risk of bias except for concerns about uncontrolled confounding.

Table 28 Evidence examining the relationship between snacking in adults and older adults and body composition and risk of obesity^a^

Study and Population Characteristics | Intervention, Comparator, and Outcome(s) | Results | Study Limitations
RANDOMIZED CONTROLLED TRIALS
Poston, 2005^83^; RCT-Parallel, U.S.; Baseline N=100, Analytic N=100 (Attrition: 0%); Study objective: To evaluate whether snacking would improve weight loss and weight maintenance in overweight individuals within the context of a prospective, randomized trial using a meal replacement weight loss program; Participant characteristics at baseline: adults participating in a meal replacement weight loss trial; - Age: ~40(8)y; - Female: 87%; - Race and/or ethnicity: White: 27%; African American: 40%; Asian: 3%; Hispanic: 30%; - Socioeconomic position: 63% with at least some college education; 60% married; - Anthropometry: BMI ~30 kg/m^2^; - Physical activity: NR; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: 50% ate 5.5 eating episodes/d ("snacker"); Excluded from study or analysis: age <35 or >55y; BMI <25 or >30 kg/m^2^; blood pressure >140/90 mmHg; insulin dependent diabetes or fasting blood glucose >126 mg/dl; prescriptions for current medications began <2mo prior to screening; no plans to remain in Houston for 1y after beginning study; pregnancy; significant conditions, diseases, or medications that could impact results of study; previous participation in weight loss study by the Nutrition Research Clinic; weight loss >10 lb during last 6mo | Intervention:; Snacks+Meal Replacement vs Meal Replacement only (hypocaloric); All participants were provided with coupons every 2wk for Slim Fast shakes, meal bars, and snack bars and were required to consume a minimum of 2 Slim Fast products a day.; Snacks+Meal Replacement (Snacks+MR): participants were told to use the Slim Fast products for meals and their 3 snacks a day; Meal Replacement only (MR only): participants were told to use the Slim Fast products for meals and were explicitly encouraged to not use any snacks and to avoid excess calories between meals; Duration: 24wk; Compliance: Daily diaries at each weekly visit for adherence counseling with registered dietitian; Outcomes and assessment methods:; - At baseline, 12wk, and 24wk follow-up; - Weight was measured. | [underlined: Weight loss (kg) at 12wk], Mean (SD); Completers analysis; MR only, habitual non-snackers (n=9): −4.17 (2.8); MR only, habitual snackers (n=15): −4.31 (2.2); Snacks+MR, habitual non-snackers (n=18): −5.36 (4.2); Snacks+MR, habitual snackers (n=15): −3.73 (2.5) p=0.983; Last observation carried forward analysis; MR only, habitual non-snackers (n=25): −1.98 (2.6); MR only, habitual snackers (n=25): −2.72 (2.6); Snacks+MR, habitual non-snackers (n=25): −3.92 (4.3); Snacks+MR, habitual snackers (n=25): −2.58 (3.0) p=0.185; [underlined: Weight loss (kg) at 24wk], Mean (SD); Completers analysis; MR only, habitual non-snackers (n=10): −4.09 (3.4); MR only, habitual snackers (n=13): −4.46 (3.4); Snacks+MR, habitual non-snackers (n=14): −5.45 (6.7); Snacks+MR, habitual snackers (n=13): −3.90 (3.0) p=0.185; Last observation carried forward analysis; MR only, habitual non-snackers (n=25): −2.08 (3.4); MR only, habitual snackers (n=25): −2.85 (3.2); Snacks+MR, habitual non-snackers (n=25): −3.48 (5.5); Snacks+MR, habitual snackers (n=25): −2.42 (3.2) p=0.629 | Model adjustments:; - TEI: yes; Limitations:; - Methods for randomization and concealment NR; - Concerns with deviations from intended intervention; - Differences in attrition; - Unclear if outcome assessors were aware of intervention assignment; - No power calculation; - No preregistered data analysis plan; Funding:; Slim Fast Corporation
OBSERVATIONAL STUDIES
Barrington, 2019^76^; PCS, secondary analysis of Physical Activity and Changes in Eating study (weight gain prevention trial), U.S.; Analytic N=1151 (258–262 in sub-sample); Study objective: To evaluate snacking patterns in relation to obesity (i.e., body mass index, waist circumference), and to obesity-related behaviors (i.e., fruit and vegetable consumption, obesogenic dietary index score, and distracted-eating); Participant characteristics at baseline: working adults; - Age: 43 (0.7)y; - Female: 52%; - Race and/or ethnicity: White: 77%; African-American: 3%; Asian: 10%; Other: 3%; Missing: 1%; Hispanic/Latino: 5%; - Socioeconomic position: Education: 15% post-graduate, 34% college graduate, 35% some college or technical college, 15% high school diploma or GED certificate; All working; 78% non-manual occupation (white or pink collar); - Anthropometry: BMI 29.0 (6.7) kg/m^2^; - Physical activity: Leisure-time 31.1 (29.2) METs-hr/wk; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: Snacking frequency 1.4 (1.1) times/d; Excluded from study or analysis: missing data on eating occasion grid or gender at baseline; missing survey data at 2y follow-up | Exposure:; Snacking frequency (0, 1, or 2 times/d in the morning, mid-day, or evening); Assessment methods and timing:; - The time and type of eating occasions was assessed using a pattern matrix. Participants wrote in the time of every eating occasion and checked which type of meal the eating occasion represented (i.e., main meal, light meal/breakfast, snack meal, or drink only). The distribution of snack times over the day was visually examined to identify natural cut-points. Based on this approach, three major snack time periods were identified including: morning (12:00 a.m. to 10:59 a.m.), mid-day (11:00 a.m. to 4:29 p.m.), and evening (4:30 p.m. to 11:59 p.m.). The number of snack occasions was summed within each snack period to obtain the frequency and grouped into frequency categories (i.e., ‘0’, ‘1’, ‘2+’).; - At baseline; Outcomes and assessment methods:; - At baseline, 2y follow-up; - Weight and height were self-reported and used to calculate BMI. A subsample had height, weight, and waist circumference (WC) measured by trained study personnel. | [underlined: WC at 2y follow-up (cm) in sub-sample (n=258) based on baseline snacking frequency], Mean (95% CI); Morning; 0 times/d: 87.4 (84.9, 90.0); 1 time/d: 85.4 (82.8, 88.2); 2 times/d: 86.5 (80.0, 93.5) p=0.37; Mid-day; 0 times/d: 87.4 (84.6, 90.4); 1 time/d: 84.9 (82.1, 87.7); 2 times/d: 91.1 (84.0, 98.7) p=0.68; Evening; 0 times/d: 84.3 (82.1, 86.6); 1 time/d: 88.6 (85.9, 91.4); 2 times/d: 99.5 (90.9, 108.9) p<0.0001; [underlined: Self-reported BMI at 2y follow-up (kg/m^2^) based on baseline snacking frequency], Mean (95% CI); Morning; 0 times/d: 26.7 (26.5, 27.5); 1 time/d: 27.1 (26.5, 27.6); 2 times/d: 26.3 (24.9, 27.9) p=0.79; Mid-day; 0 times/d: 27.0 (26.5, 27.5); 1 time/d: 26.8 (26.3, 27.3); 2 times/d: 27.9 (26.4, 29.4) p=0.95; Evening; 0 times/d: 26.3 (25.9, 26.8); 1 time/d: 28.0 (27.4, 28.6); 2 times/d: 28.0 (26.3, 29.9) p<0.0001; [underlined: Measured BMI at 2y follow-up (kg/m^2^) in subsample (n=262) based on baseline snacking frequency], Mean (95% CI); Morning; 0 times/d: 29.1 (28.2, 30.2); 1 time/d: 28.6 (27.5, 29.7); 2 times/d: 28.3 (25.5, 31.4) p=0.43; Mid-day; 0 times/d: 28.4 (27.4, 29.4); 1 time/d: 29.1 (28.1, 30.2); 2 times/d: 31.0 (28.1, 34.2) p=0.11; Evening; 0 times/d: 28.1 (27.2, 29.0); 1 time/d: 29.4 (28.3, 30.6); 2 times/d: 34.8 (31.0, 39.1) p=0.001 | Model adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, physical activity; - Other: presence/absence of a main or light meal for the corresponding snack period; Limitations:; - Did not account for key confounders: anthropometry at baseline, smoking; - Exposure data only assessed at baseline leading to a concern that changes in exposure status occurred over 2y f/u; - No information on non-completers; - Weight was self-reported; - No preregistered data analysis plan; - Did not adjust for TEI; Funding:; NHLBI; NCI
Bes-Rastrollo, 2010^77^; PCS, SUN Project, Spain; Analytic N=10,162; Study objective: To prospectively assess the relationship between snacking and weight gain and obesity in a middle-aged free-living population; Participant characteristics at baseline: middle-aged adults; - Age: 39 (0.11)y; - Female: 54%; - Race and/or ethnicity: NR; - Socioeconomic position: All university graduates; - Anthropometry: BMI 23.8 (0.02) kg/m^2^; - Physical activity: 24.6 (0.21) METs-hr/wk; - Smoking: 23% current, 29% former; - TEI: 2364 (7) kcal/d among non-snackers; 2455 (11) kcal/d among usual snackers; - Habitual diet at baseline: 38% reported between-meal snacking; Excluded from study or analysis: extreme values for total energy intake (<800 of >4000 kcal/d for men; <500 or >3500 kcal/d for women); special diet (hypocaloric, low-cholesterol, low-fat, low-salt); pregnant; missing data on snacking or covariates | Exposure:; Snacking frequency (non-snackers vs usual snackers); Assessment methods and timing:; - "Do you usually eat between meals (snacking)? Yes/No"; - At baseline; Outcomes and assessment methods:; - At baseline, every 2y during follow-up (mean 4.6y); - Weight and height were self-reported and used to calculate BMI. Substantial weight gain defined as ≥3kg/yr during follow-up. Incident obesity defined as BMI ≥30 kg/m^2^ during follow-up. | [underlined: Change in weight (g/yr) during follow-up], Mean (95% CI) Non-snackers: 136 (62, 208); Usual snackers: 196 (121, 271) p=0.006; [underlined: Change in weight (g/yr) during follow-up], β (95% CI); Usual snacking: 57 (13, 100), p=0.011; [underlined: ≥3kg weight gain per year], OR (95% CI); Total sample; Non-snackers: REF; Usual snackers: 1.50 (1.05, 2.14); Stratified by baseline BMI; [underlined: Underweight (BMI <18.5 kg/m^2^)]; Non-snackers: REF; Usual snackers: 3.25 (0.49, 21.67); [underlined: Normal weight (BMI 18.5 –24.9 kg/m^2^)]; Non-snackers: REF; Usual snackers: 1.94 (1.18, 3.18); [underlined: Overweight (BMI 25–29.9 kg/m^2^)]; Non-snackers: REF; Usual snackers: 1.18 (0.64, 2.19); [underlined: Obesity (BMI ≥30 kg/m^2^)]; Non-snackers: REF; Usual snackers: 1.88 (0.63, 5.58); [underlined: ≥3kg weight gain per yea]r, OR (95% CI); Usual snacking: 1.66 (1.17, 2.35), p=0.005; [underlined: Obesity (BMI ≥30 kg/m^2^)], HR (95% CI); Non-snackers: REF; Usual snackers: 1.63 (1.26, 2.12); Usual snacking: 1.69 (1.30, 2.20), p<0.001 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, anthropometry at baseline, physical activity, smoking; - Other: TV viewing; sitting; fast food consumption; SSB consumption; alcohol intake; total fiber intake; meat consumption; fruit and vegetable consumption; Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position; - Exposure data only assessed at baseline leading to a concern that changes in exposure status occurred over 4y f/u; - No information on non-completers; - Weight was self-reported; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; Funding:; Spanish Ministry of Health; Navarra Regional Government; University of Navarra
Elahy, 2023^14^; PCS, secondary analysis of Innovative Approaches to Diet, Exercise and Activity (IDEA) trial, U.S.; Analytic N=372; Study objective: To estimate the effect of hypothetical interventions of higher and lower frequency of breakfast and post-dinner snack consumption on changes in body weight and composition over 18 months after a successful 6mo standard behavioral weight-loss program; Participant characteristics at baseline: young adults with overweight or obesity; - Age: 30.1 (3.8)y; - Female: 71%; - Race and/or ethnicity: White: 82%; Black: 15%; Asian: 3%; - Socioeconomic position: Education: 23% high school/GED/some college, 42% bachelors degree, 35% graduate degree; Annual household income: 39% <$5k, 43% $5k-<$12k, 17% $12k-<$16k; - Anthropometry: BMI 31.7 (4) kg/m^2^; - Physical activity: <150 min/wk moderate PA: 76%; <75 min/wk vigorous PA: 35%; - Smoking: 8% current; - TEI: 1900.5 (866.7) kcal/d; - Habitual diet at baseline: 66% eat breakfast 5–7x/wk; 97% eat dinner 5–7x/wk; 34% eat post-dinner snack 5–7x/wk; Excluded from study or analysis: BMI <25 or >40 kg/m^2^; <18 or >35y; had past or planned weight loss surgery; current participation in another weight loss intervention study; incomplete questions on breakfast frequency, evening snack frequency, body composition, and weight data at baseline and 6mo follow-up; implausible energy intake (<600 or >6000 kcal/d for women and <800 or >8000 kcal/d for men) | Exposure:; Post-dinner snack (0–2 vs 3–7 times/wk); Post-dinner snack was implied to occur separately and after a dinner meal. Post-dinner snack frequency was categorized as frequent to habitual post-dinner snack frequency (consumption of post-dinner snack 3–7 times/wk) and avoidance to rare post-dinner snack frequency (consumption of post-dinner snack 0–2 times/wk).; Assessment methods and timing:; - A daily meal patterns survey was used to assess frequency of meals and snacks. Participants were asked "In a typical week, how many times do you eat…?" and answers were 0, 1–2, 3–4, 5–6, and 7 times.; - At baseline (after 6mo trial), and 6-, 12-, and 18-month follow-up; Outcomes and assessment methods:; - At baseline (after 6mo trial), and 18-month follow-up; - Weight was measured and body composition (fat mass and lean mass) was assessed using DEXA. Absolute changes in weight and body composition were calculated as the difference between 18-mo values and baseline values. | [underlined: Change in body fat mass (kg) over 18mo follow-up]; Per-protocol; Within groups: Mean change (95% CI) 0–2x/wk: 2.29 (0.95, 4.12); 3–7x/wk: 2.89 (1.44, 3.87); Between groups: Mean difference (95% CI); 3–7x/wk (REF) vs 0–2x/wk: −0.59 (−0.78, −0.39); Intent-to-treat; Within groups: Mean change (95% CI) 0–2x/wk: 1.8 (−0.42, 3.5); 3–7x/wk: 3.14 (1.07, 4.57); Between groups: Mean difference (95% CI); 3–7x/wk (REF) vs 0–2x/wk: −1.23 ( −1.27, −1.19); [underlined: Change in body lean mass (kg) over 18mo follow-up]; Per-protocol; Within groups: Mean change (95% CI) 0–2x/wk: 0.58 (0.12, 1.22); 3–7x/wk: 0.8 (0.47, 1.09); Between groups: Mean difference (95% CI); 3–7x/wk (REF) vs 0–2x/wk: −0.22 (−0.29, −0.16); Intent-to-treat; Within groups: Mean change (95% CI) 0–2x/wk: 0.65 (0.18, 1.12); 3–7x/wk: 0.58 (0.16, 1.04); Between groups: Mean difference (95% CI) 3–7x/wk (REF) vs 0–2x/wk: 0.05 (0.04, 0.06); [underlined: Change in body weight (kg) over 18mo follow-up]; Per-protocol; Within groups: Mean change (95% CI) 0–2x/wk: 2.86 (0.99, 5.25); 3–7x/wk: 3.7 (2.29, 4.9); Between groups: Mean difference (95% CI); 3–7x/wk (REF) vs 0–2x/wk: −0.83 ( −1.06, −0.59); Intent-to-treat; Within groups: Mean change (95% CI) 0–2x/wk: 2.43 (0.18, 4.32); 3–7x/wk: 3.72 (1.56, 5.29); Between groups: Mean difference (95% CI); 3–7x/wk (REF) vs 0–2x/wk: −1.18 ( −1.22, −1.14) | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, physical activity, smoking; - Other: breakfast frequency; post-dinner snack frequency; alcohol consumption; sleep duration; diet quality; depression; Limitations:; - Exposure assessment method not validated; - Water/Beverages were not accounted for in exposure assessment; Funding:; Funding NR
Larsen, 2019^80^; PCS, Danish Monitoring Trends and Determinants in Cardiovascular Disease (MONICA) study, Denmark; Analytic N=2,124; Study objective: To examine the associations between eating frequency and 6-y changes in BMI, fat mass, fat-free mass, body fat percentage, and waist circumference.; Participant characteristics at baseline: middle-aged adults; - Age: 46 (36–66)y; - Female: 49%; - Race and/or ethnicity: NR; Socioeconomic position: 30% ≤ primary level education; - Anthropometry: BMI 24 (20–32) kg/m^2^; - Physical activity: 23% inactive/sedentary; - Smoking: 50% never; - TEI: NR; - Habitual diet at baseline: Eats 4 (2, 6) times/d; 3 (2, 4) meals per day and 1 (0, 3) snacks per day; Excluded from study or analysis: missing data on eating frequency, adiposity measures, or covariates; prevalent cancer, cardiovascular disease, self-reported diabetes prior to health exam | Exposure:; Snacking frequency (times/d); Assessment methods and timing:; - Participants completed a survey and reported how many meals they ate during the day and how often they snacked between meals.; - At T1 (1982–1983), and T2 (1987–1988); Outcomes and assessment methods:; - At T1 (1982–1983), T2 (1987–1988), and T3 (1993–1994); - Height, weight, and waist circumference (WC) were measured. Body fat percentage (BF%) was measured using bioelectric impedance. BMI, fat-mass index (FMI), and fat-free mass index (FFMI) were calculated. | [underlined: 6y change in FMI (kg/m^2^) from T2-T3], β (95% CI); Based on snacking frequency at T2; 0.03 (−0.01, 0.08), p=0.13; Based on 5yΔ in snacking frequency from T1-T2; 0.05 (0.00, 0.09), p=0.04; [underlined: 6y change in FFMI (kg/m^2^) from T2-T3], β (95% CI); Based on snacking frequency at T2; −0.01 (−0.03, 0.01), p=0.36; Based on 5yΔ in snacking frequency from T1-T2; −0.00 (−0.02, 0.02), p=0.79; [underlined: 6y change in BF% from T2-T3], β (95% CI); Based on snacking frequency at T2; 0.09 (−0.01, 0.19), p=0.07; Based on 5yΔ in snacking frequency from T1-T2; 0.12 (0.02, 0.23), p=0.02; [underlined: 6y change in WC (cm) from T2-T3], β (95% CI); Based on snacking frequency at T2; −0.00 (−0.22, 0.21), p=0.99; Based on 5yΔ in snacking frequency from T1-T2; 0.09 (−0.14, 0.32), p=0.43; Among subsample (n=314) with TEI:; p=NS for FMI, FFMI, BF%, and WC; p=NS for effect modification by gender or obesity status; [underlined: 6y change in BMI (kg/m^2^) from T2-T3], β (95% CI); Based on snacking frequency at T2; 0.03 (−0.03, 0.08), p=0.38; Based on 5yΔ in snacking frequency from T1-T2; 0.05 (−0.01, 0.11), p=0.13; Among subsample (n=314) with TEI:; p=NS for BMI; p=NS for effect modification by gender or obesity status | Model adjustments:; - TEI: yes, in a subsample of 314 participants; - Key confounders: sex, age, socioeconomic position, anthropometry at baseline, physical activity, smoking; - Other: alcohol intake; menopausal status for women; height (for WC); baseline intake of snacks or meals; Limitations:; - Did not account for key confounders: race and/or ethnicity; - Exposure assessment method not validated; - High attrition rate/missing data; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; - Did not adjust for TEI in full sample; Funding:; No external funding
Nishiura, 2010^48^; PCS, Japan; Analytic N=2,632; Study objective: To investigate whether dietary patterns explain the possible association between short sleep duration and obesity.; Participant characteristics at baseline: Non-obese Japanese male workers (40–59y); - Age: ~47 (5)y; - Female: 0%; - Race and/or ethnicity: NR, but likely majority Asian; - Socioeconomic position: Majority white-collar workers; - Anthropometry: BMI ~22 (2) kg/m^2^; - Physical activity: 37% currently exercise; - Smoking: 57% current; - TEI: NR; - Habitual diet at baseline: 16% skip breakfast; 6% snack; Excluded from study or analysis: BMI >25 kg/m^2^ at baseline; missing or incomplete data at baseline; those lost at follow-up | Exposure:; Snacking (yes/no); Assessment methods and timing:; - Lifestyle questionnaire at annual health checkup, which included yes/no questions on skipping breakfast and snacking; - At baseline; Outcomes and assessment methods:; - At baseline, 4y follow-up; - Height and weight were measured at annual health exam and used to calculate BMI. Obesity was defined as BMI ≥25 kg/m^2^ based on criteria determined by Japan Society for the Study of Obesity | [underlined: Obesity (BMI≥25 kg/m^2^)], OR (95% CI) Not snacking: REF; Snacking: 2.10 (1.21, 3.65) | Model adjustments:; - TEI: no; - Key confounders: sex; - Other: none; Limitations:; - Did not account for key confounders: age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, physical activity, smoking; - Exposure assessment method not validated; - Exposure data only assessed at baseline leading to a concern that changes in exposure status occurred over 4y f/u; - High attrition rate/missing data; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; No industry funding.
Odegaard, 2013^50^; PCS, Coronary Artery Risk Development in Young Adults (CARDIA), U.S.; Analytic N=1138 (abdominal obesity); 1064 (obesity); Study objective: To examine breakfast intake frequency with incidence of metabolic conditions; Participant characteristics at baseline: young black and white adults; - Age: ~32(3)y; - Female: 56%; - Race and/or ethnicity: White: 54%; Black: 46%; - Socioeconomic position: Education: ~14(2)y; - Anthropometry: BMI ~26(6) kg/m^2^; - Physical activity: ~330 exercise units/wk; - Smoking: 26% current; 16% former; - TEI: ~2760 (1200) kcal/d; - Habitual diet at baseline: 43% ate breakfast 0–3 days/wk, 22% 4–6 days/wk, and 35% daily; Excluded from study or analysis: did not participate in any clinical exam in years 10–25; diabetes at baseline; missing dietary data or with reported energy intakes outside 800–8,000 kcal/day for men and 600–6,000 kcal/day for women; missing data on alcohol, smoking, or physical activity); participants prevalent with the condition at year 7 | Exposure:; Morning, afternoon, and evening snack frequency (days/wk); Assessment methods and timing:; - Interview-administered CARDIA diet history questionnaire; - Baseline (year 7), and year 20; Outcomes and assessment methods:; - Baseline (year 7), and years 10, 15, 20, and 25; - Height, weight, and waist circumference were measured by staff at each clinical examination. Obesity defined as BMI ≥30 kg/m^2^ and abdominal obesity as waist circumference >88cm for women or >102 cm for men. | [underlined: Abdominal obesity], HR (95% CI); p=NS, data not shown; Obesity, HR (95% CI) p=NS, data not shown | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, physical activity, smoking; - Other: study center; alcohol consumption; fast food restaurant use; diet quality score; frequency of lunch/dinner and morning/afternoon/evening snacks; Limitations:; - Did not account for those with missing data; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; Funding:; NHLBI; NIDDK; Bell Institute of Health and Nutrition at General Mills
Phelan, 2008^52^; PCS, National Weight Control Registry, U.S.; Analytic N=257 (post-holiday); 252 (1mo f/u); Study objective: To systematically compare the behaviors of successful weight losers vs normal weight losers before, during, and after the winter holiday season; Participant characteristics at baseline: adults with successful weight loss; - Age: ~46 (12)y; - Female: 75%; - Race and/or ethnicity: Caucasian: 96%; - Socioeconomic position: 73% ≥college education; - Anthropometry: BMI 25.5 (6.4) kg/m^2^ among successful weight losers; 21.8 (1.9) kg/m^2^ among normal weight participants; - Physical activity: NR; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: NR; Excluded from study or analysis: age <18y; among successful weight losers, those that did not maintain weight loss ≥30 lbs for ≥1 yr; among normal weight participants, those with BMI <18.5 or ≥25 kg/m^2^ | Exposure:; Snacking frequency (days/wk); Assessment methods and timing:; - “Over the past month, on average how many days per week did you eat (breakfast, lunch, dinner, snacks, and dessert/sweets); - Before the holiday (Nov), and after the holiday (Jan); Outcomes and assessment methods:; - Before the holiday (Nov), after the holiday (Jan), and at 1mo follow-up (Feb); - Weight was self-reported | [underlined: Change in weight over 2mo (pre-holiday to post-holiday) based on pre-holiday snacking frequency]; Data NR, p=NS; [underlined: Change in weight over 3mo (pre-holiday to 1mo after the holiday) based on pre-holiday snacking frequency]; Data NR, p=NS | Model adjustments:; - TEI: no; - Key confounders: anthropometry at baseline; - Other: none; Limitations:; - Did not account for key confounders: sex, age, race and/or ethnicity, socioeconomic position, physical activity, smoking; - Selection into study maybe have been related to exposure and outcome; - High attrition rate; - Weight was self-reported; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; Funding NR
Pimenta, 2016^82^; PCS, SUN Project, Spain; Analytic N=6,851; Study objective: To longitudinally evaluate the association of snacking between main meals with the risk of metabolic syndrome in large Mediterranean cohort with a prolonged follow-up; Participant characteristics at baseline: adults initially free of metabolic syndrome; - Age: ~34(9)y; - Female: 60%; - Race and/or ethnicity: NR; - Socioeconomic position: All university graduates (~36% technical degree or non-graduated; ~14% master/doctoral degree); ~43% married; - Anthropometry: BMI 22 (2.7) kg/m^2^; - Physical activity: ~21 (23) MET-hr/wk; - Smoking: ~24% current; - TEI: ~2400 kcal/d; - Habitual diet at baseline: 38% reported between-meal snacking; Excluded from study or analysis: diabetes or any metabolic syndrome criterion at baseline; extreme values for total energy intake (<800 of >4000 kcal/d for men; <500 or >3500 kcal/d for women); missing follow-up data; missing metabolic syndrome component data and/or >9 items on FFQ at baseline | Exposure:; Snacking between main meals (yes/no); Assessment methods and timing:; - "Do you have the habit of snacking between main meals? Yes/No". Participants were not provided with a specific definition of 'main meals'.; - At baseline; Outcomes and assessment methods:; - At ≥6y follow-up (median 8.3y); - Participants were provided with instructions on how to measure their own waist circumference. Central adiposity was defined as ≥94cm for men and ≥80cm for women based on cut-off points for European populations. | [underlined: Central adiposity], RR (95% CI) No snacking: REF; Snacking: 1.02 (0.95, 1.10) p=0.614 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, socioeconomic position, anthropometry at baseline, physical activity, smoking; - Other: Mediterranean diet adherence; eating away-from-home meals; television watching; Limitations:; - Did not account for key confounders: race and/or ethnicity; - Exposure data only assessed at baseline leading to a concern that changes in exposure status occurred over f/u; - Waist circumference was self-reported; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; Funding:; Spanish Ministry of Health and European Regional Development Fund; Navarra Regional Government; University of Navarra
Seki, 2021^57^; RCS, Japan Medical Data Center Co., Ltd. - Specific Health Checkup Database, Japan; Analytic N=123,182; Study objective: To evaluate various eating and drinking habits and the risk of obesity using a large-scale health check-up database; Participant characteristics at baseline: healthy Japanese adults; - Age: Median 45y (IQR: 40–51y); - Female: 37%; - Race and/or ethnicity: NR, but likely majority Asian; - Socioeconomic position: All employed (mainly for large-scale companies); - Anthropometry: Median BMI 23.1 kg/m^2^; - Physical activity: 21% exercise ≥30min on ≥2d/wk; - Smoking: 29% current; - TEI: NR; - Habitual diet at baseline: 17% skip breakfast; 14% snack late at night; Excluded from study or analysis: aged <19y; missing baseline data; history of heart disease, stroke or kidney disease; BMI ≥25 kg/m^2^ or WC ≥85 cm for men and ≥90cm for women at baseline; did not receive a health exam at 5y follow-up | Exposure:; Snacking after dinner (yes/no); Assessment methods and timing:; - Questionnaire on eating and drinking habits, including: "I have a snack after dinner at least 3 times a week: yes/no"; - At baseline; Outcomes and assessment methods:; - At baseline, 5y follow-up; - Height, weight, and waist circumference (WC) were measured at annual health exam; height and weight were used to calculate BMI. Obesity was defined as BMI ≥25 kg/m^2^ based on criteria determined by Japan Society for the Study of Obesity. Abdominal obesity defined as WC≥85cm for men and WC≥90cm for women. | [underlined: Abdominal obesity], OR (99% CI); Not snacking after dinner: REF; Snacking after dinner: 1.03 (0.93, 1.14) p=0.43; [underlined: Change in WC over 5y follow-up (cm) by baseline snacking], β (SE); 0 (−0.09, 0.09), p=0.96; [underlined: Obesity (BMI≥25 kg/m^2^)], OR (99% CI); Not snacking after dinner: REF; Snacking after dinner: 1.09 (1.01, 1.18) p=0.006; [underlined: Change in BMI over 5y follow-up (kg/m^2^) by baseline snacking], β (SE); −0.01 (−0.04, 0.01), p=0.26 | Model adjustments:; - TEI: no; - Key confounders: sex, age, anthropometry at baseline, physical activity, smoking; - Other: insufficient sleep; measured laboratory values (systolic BP, diastolic BP, LDL, HDL, TAG, AST, ALT, GGT); weight gain ≥10kg from 20 years; weight gain ≥3kg in preceding year; drug use for hypertension, dyslipidemia, and diabetes; calendar year at baseline; frequency of drinking; amount of alcohol; eating speed; Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position; - Exposure data only assessed at baseline leading to a concern that changes in exposure status occurred over 5y f/u; - No information on non-completers; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; Suntory Beverage & Food Ltd; Japan Agency for Medical Research and Development
Tokumaru, 2020^65^; RCS, Japan; Analytic N=26,764; Study objective: To investigate the association between unhealthy dietary habits and proteinuria onset, which is a key prognostic factor of chronic kidney disease; Participant characteristics at baseline: Japanese older adults; - Age: 68 (9)y; - Female: 56%; - Race and/or ethnicity: NR, but likely majority Asian; - Socioeconomic position: NR; - Anthropometry: BMI 22.8 (3.1) kg/m^2^; - Physical activity: NR; - Smoking: 14% current; - TEI: NR; - Habitual diet at baseline: 9% skip breakfast; 16% eat late evening snack; Excluded from study or analysis: <40y; glomerular filtration rate <60 mL/min/1.73 m^2^; follow-up period <1 year; baseline urinary protein dipstick result of ≥1+; missing data on status of dietary habits or other covariates | Exposure:; Eating snacks after dinner ≥3 times/wk (yes/no); Assessment methods and timing:; - Questionnaire on unhealthy dietary habits, including skipping breakfast and late evening snacking.; - At baseline; Outcomes and assessment methods:; - At baseline, 5y follow-up; - Height, weight, and waist circumference were measured during the health exam. Weight and height were used to calculate BMI, and waist circumference and height were used to calculate waist-to-height ratio. | [underlined: Change in waist-to-height ratio (cm/cm) over 5y follow-up], Mean (95% CI); Data NR (figure only), p=0.653; [underlined: Change in BMI (kg/m^2^) over 5y follow-up], Mean (95% CI); Data NR (figure only), p=0.818 | Model adjustments:; - TEI: no; - Key confounders: sex, age, anthropometry at baseline, smoking; - Other: systolic blood pressure; estimated glomerular filtration rate; hemoglobin; triglyceride; total cholesterol; HbA1c; serum uric acid; daily drinking; Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position, physical activity; - Exposure data only assessed at baseline leading to a concern that changes in exposure status occurred over 5y f/u; - No information on non-completers; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; No external funding
Yoshida, 2018^85^; PCS, Japan; Analytic N=8,153; Study objective: To assess whether the presence of both night eating habits was associated with metabolic syndrome and its components, such as obesity, abdominal obesity, dyslipidemia, impaired blood pressure, and impaired blood glucose; Participant characteristics at baseline: middle-aged adults; - Age: 46.8 (0.2)y; - Female: 40%; - Race and/or ethnicity: NR, but likely majority Asian; - Socioeconomic position: NR; - Anthropometry: BMI 22.9 (0.1) kg/m^2^; - Physical activity: 17% walk or perform equivalent physical activity ≥1hr/d; - Smoking: 28% current; - TEI: NR; - Habitual diet at baseline: 12% snack after dinner ≥3 times/wk; Excluded from study or analysis: aged <40 or >55y; missing data on "dinner immediately before bed" and "snacks after dinner" | Exposure:; Snacks after dinner ≥3 times/wk vs not snacking; Assessment methods and timing:; - Yes/no question on night eating habits, such as "dinner immediately before bed" (dinner within 2hr of bedtime ≥3 times/wk) and "snacks after dinner" ≥3 times/wk; - At baseline (2009–2010); Outcomes and assessment methods:; - At baseline (2009–2010), and 4y follow-up (2013–2014); - Height, weight, and waist circumference were measured at annual health exam. Weight and height were used to calculate BMI. Obesity was defined as BMI ≥25 kg/m^2^ based on WHO criteria. Abdominal obesity was defined as a waist circumference ≥90cm for men and ≥80cm for women. | [underlined: Abdominal obesity], OR (95% CI); All Participants; No snacking: REF Snacking: 1.19 (0.91, 1.55); Male Participants; No snacking: REF Snacking: 1.13 (0.70, 1.84); Female Participants; No Snacking: REF Snacking: 1.19 (0.87, 1.65); [underlined: Obesity (BMI >25 kg/m^2^)], OR (95% CI); All Participants; No snacking: REF Snacking: 1.32 (0.95, 1.84); Male Participants; No snacking: REF Snacking: 1.60 (1.02, 2.49); Female Participants; No Snacking: REF Snacking: 1.05 (0.64, 1.74) | Model adjustments:; - TEI: no; - Key confounders: sex, age, physical activity, smoking; - Other: alcohol consumption; breakfast intake; hypertension; dyslipidemia; hyperglycemia; Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position, anthropometry at baseline; - Exposure data only assessed at baseline leading to a concern that changes in exposure status occurred over f/u; - Exposure assessment only captured evening snacks and not total frequency of snacking; - High attrition rate/missing data; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; No external funding

a Abbreviations: ALT: alanine aminotransferase; AST: aspartate aminotransferase; AUD: Australian Dollar; β: beta coefficient; BMI: body mass index; BMIz: body mass index z-score; BP: blood pressure; CDC: Centers for Disease Control and Prevention; CI: confidence interval; cm: centimeter(s); d: day(s); DEXA: dual energy x-ray absorptiometry; FFQ: food frequency questionnaire; g: gram(s); GGT: gamma-glutamyl transferase; HbA1c: hemoglobin A1C; HOMA-IR: Homeostatic Model Assessment of Insulin Resistance; hr: hour(s); HR: hazard ratio; IOTF: International Obesity Task Force; IQR: interquartile range; kcal: kilocalorie(s); kg: kilogram(s); lb: pound(s); m: meter(s); MET: metabolic equivalent; min: minute(s); mm: millimeter(s); MVPA: moderate to vigorous physical activity; N/A: not applicable; NCC: nested case control study; NCI: National Cancer Institute; NHLBI: National Heart, Lung, and Blood Institute; NICHD; Eunice Kennedy Shriver National Institute of Child Health and Human Development; NIDDK: National Institute of Diabetes and Digestive and Kidney Diseases; NIH: National Institutes of Health; NISOC: nmol: nanomole; NR: not reported; NS: not significant; OR: odds ratio; PCS: prospective cohort study; Project EAT: Project Eating and Activity over Time; RCS: retrospective cohort study; REF: reference group; RMB: renminbi (Chinese yuan); RR: risk ratio; SD: standard deviation; SDS: standard deviation score; SE: standard error; SEP: socioeconomic position; SES: socioeconomic status; svg: serving(s); TAG: triacylglycerol; TEI: total energy intake; wk: week(s); x: time(s); y: year(s)

Table 29 Risk of bias for randomized controlled trials examining snacking in adults and older adults and body composition and risk of obesity^a^

Article | Randomization | Deviations from intended interventions (effect of assignment) | Missing outcome data | Outcome measurement | Selection of the reported result | Overall risk of bias
Poston, 2005^83^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | SOME CONCERNS

a Possible ratings of low, some concerns, or high determined using the "Cochrane Risk-of-bias 2.0" (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898. doi:10.1136/bmj.l4898.31462531 )

Table 30 Risk of bias for observational studies examining snacking in adults and older adults and body composition and risk of obesity^b^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Barringon, 2019^76^ | HIGH | SOME CONCERNS | LOW | LOW | HIGH | SOME CONCERNS | SOME CONCERNS | HIGH
Bes-Rastrollo, 2010^77^ | HIGH | SOME CONCERNS | LOW | LOW | HIGH | SOME CONCERNS | HIGH | HIGH
Elahy, 2023^14^ | LOW* | SOME CONCERNS | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Larsen, 2019^80^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Nishiura, 2010^48^ | VERY HIGH | VERY HIGH | LOW | LOW | HIGH | LOW | HIGH | VERY HIGH
Odegaard, 2013^50^ | LOW* | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Phelan, 2008^52^ | HIGH | SOME CONCERNS | LOW | LOW | HIGH | HIGH | SOME CONCERNS | HIGH
Pimenta, 2016^82^ | SOME CONCERNS | HIGH | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH
Seki, 2021^57^ | SOME CONCERNS | HIGH | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Tokumaru, 2020^65^ | HIGH | HIGH | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Yoshida, 2018^85^ | HIGH | VERY HIGH | LOW | LOW | HIGH | LOW | SOME CONCERNS | VERY HIGH

b Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the "Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)" tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602 .) *Low risk of bias except for concerns about uncontrolled confounding.

Table 31 Evidence examining the relationship between number of eating occasions in children and adolescents and growth, body composition, and risk of obesity^a^

Study and Population Characteristics | Intervention, Comparator, and Outcome(s) | Results | Study Limitations
Arenaza, 2020^86^; PCS, Secondary analysis of EFIGRO NRCT, Spain; Analytic N=81; Study objective: To examine the effectiveness of a 22-week family-based lifestyle education program on dietary habits, and to explore the associations of changes in dietary intake with percent hepatic fat reduction and adiposity in children with overweight/obesity; Participant characteristics at baseline: children with overweight or obesity; - Age: 10.6 (1.1)y; - Female: 53%; - Race and/or ethnicity: 73% with Spanish-origin mother; - Socioeconomic position: 72% high educational level of mother (high not defined); - Anthropometry: BMI ~25 (3) kg/m^2^; 55% with obesity; - Physical activity: NR; - Smoking: NR; - TEI: ~1840 kcal/d; - Habitual diet at baseline: <1% skip breakfast; 90% eat >4 meals/d; Excluded from study or analysis: did not complete study or attend at least 50% of lifestyle education sessions; missing 24-h recalls at baseline and post-intervention | Exposure: Number of eating occasions (times/d); An eating occasions was defined as ≥50 kcal/meal and ≥15min from any other eating occasion; Assessment methods and timing:; - Two 24-h recalls; - At baseline, 22wk; Outcomes and assessment methods:; - At baseline, 22wk; - Fat mass and abdominal fat were measured using DEXA. | [underlined: Change in fat mass index (kg/m^2^) by change in eating frequency over 22wk]; All participants: r=−0.105, p=0.414 Control group: r=−0.155, p=0.346 Exercise group: r=0.075, p=0.753; [underlined: Change in abdominal fat (kg) by change in eating frequency over 22wk]; All participants: r=−0.081, p=0.528 Control group: r=−0.134, p=0.417 Exercise group: r=0.079, p=0.740 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, anthropometry at baseline; - Other: intervention group; Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position, physical activity; - Exposure was not well defined and was subject to measurement error; - Did not provide evidence as to whether the result was unbiased due to missing data; - No preregistered data analysis plan; - Water was not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; Spanish Ministry of Industry and Competitiveness; European Regional Development Funds; University of the Basque Country
Bernabe-Ortiz, 2020^88^; PCS, Young Lives Study, Peru; Analytic N=1,810; Study objective: To assess the association between daily food frequency and body mass index changes; Participant characteristics at baseline: children from cohort with oversampling of poor areas; - Age: 4.3 (0.3)y; - Female: 49%; - Race and/or ethnicity: NR but likely majority Hispanic; - Socioeconomic position: 48% maternal education <7y; 34% paternal education <7y; 38% low SES; - Anthropometry: BMI ~16.5 kg/m^2^; - Physical activity: NR; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: Eating frequency: 4.9 (1.0, range: 2–7) times per day; 5 times/day: 43.5%, <4 times/day: 11%; >7 times/day: 4%; Excluded from study or analysis: lost to follow-up; missing data | Exposure: Number of eating occasions (<4, 4, 5, 6, 7 times/day); Assessment methods and timing:; - Parents responded to 7 questions on food frequency: "During the previous 24 hours period, did the child consume: any food before a morning meal (breakfast)? Any morning meal (breakfast)? Any food between morning and midday meals? Any midday meal? Any food between midday and evening meals? Any evening meal? Any food after the evening meal?" Responses were given as yes/no, and the variable was categorized as <4, 4, 5, 6 and 7 times per day.; - At baseline (2006–2007), and 3 follow-ups (2009–2010, 2013–2014, and 2016–2017); Outcomes and assessment methods:; - At baseline (2006–2007), and 3 follow-ups (2009–2010, 2013–2014, and 2016–2017); - Height and weight were measured by study personnel and used to calculate BMI and BMI z-scores, based on the WHO reference | [underlined: Change in BMI (kg/m^2^) by change in eating frequency over 10y], β (95% CI); <4 times/d: 0.39 (0.17, 0.62), p<0.05; 4 times/d: 0.16 (0.02, 0.30), p<0.05; times/d: REF; times/d: −0.03 (−0.15, 0.09), p=NS; times/d: 0.08 (−0.33, 0.50), p=NS; [underlined: Change in BMIz by change in eating frequency over 10y], β (95% CI); <4 times/d: 0.07 (0.01, 0.13), p<0.05; 4 times/d: 0.05 (0.01, 0.09), p<0.05; times/d: REF; times/d: −0.01 (−0.05, 0.04), p=NS; times/d: 0.04 (−0.13, 0.20), p=NS | Model adjustments:; - TEI: no; - Key confounders: sex, age, socioeconomic position, anthropometry at baseline; - Other: setting (urban vs rural); maternal BMI; Limitations:; - Did not account for key confounders: race and/or ethnicity, physical activity; - Exposure was subject to measurement error; - Did not provide evidence as to whether the result was unbiased due to missing data; - No preregistered data analysis plan; - Water was not accounted for in exposure assessment; Did not adjust for TEI; Funding:; Wellcome Trust International Training Fellowship
Evans, 2015^90^; PCS, Secondary analysis of Daily D Study trial, U.S.; Analytic N=155; Study objective: To assess the cross-sectional and prospective relationships of weekday eating frequency with BMI z-score and change in BMIz in a sample of schoolchildren; Participant characteristics at baseline: 4th-8th graders; - Age: 11.4 (1.5)y; - Female: 52%; - Race and/or ethnicity: White: 44%; Black: 12%; Asian: 14%; Other: 20%; Hispanic: 11% Socioeconomic position: 52% no maternal college education; 64% free- or reduced-price lunch; - Anthropometry: BMI 21.5 (5.0) kg/m^2^; 46% overweight or obesity;; - Physical activity: 64% inactive (<150 min/wk); - Smoking: NR; - TEI: NR; - Habitual diet at baseline: Weekday eating frequency: 4.5 (1.0) eating occasions (range 2.0–8.5); Excluded from study or analysis: missing dietary or anthropometric data | Exposure: Number of eating occasions per day (times/d; infrequent eaters vs average eaters vs frequent eaters); - Infrequent Eaters: 1.0 to 3.5 eating occasions per day; - Average Eaters: 4.0 to 4.5 eating occasions per day; - Frequent Eaters: ≥5 eating occasions per day; An eating occasion was defined as any distinct time (≥15min from another eating occasion) when participant consumed at least one food or beverage (excluding water), regardless if it was designated as a meal or snack.; Assessment methods and timing:; - Two non-consecutive weekday 24-hr recalls; - At baseline; Outcomes and assessment methods:; - At baseline, 6mo, 1y; - Height and weight were measured by study personnel and used to calculate BMI z-scores using CDC reference values | [underlined: Change in BMI z-score by baseline eating frequency], β (95% CI); At 6mo:; Per each additional eating occasion: 0.03 (0.01, 0.05); Infrequent eaters: REF; Average eaters: 0.04 (−0.01, 0.09); Frequent eaters: 0.09 (0.04, 0.13); At 1y:; Per each additional eating occasion: 0.01 (−0.01, 0.03); Infrequent eaters: REF; Average eaters: 0.01 (−0.05, 0.07); Frequent eaters: 0.02 (−0.06, 0.10) | Model adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, physical activity; - Other: school; Limitations:; - Exposure was subject to measurement error and measured only once at baseline; - Did not provide evidence as to whether the result was unbiased due to missing data; - No preregistered data analysis plan; - Water was not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; NIH; NIDDK
Juton, 2023^94^; PCS, Secondary analysis of Prevention of Childhood Obesity: A Community-Based Model (POIBC intervention), Spain; Analytic N=1,400; Study objective: To determine the prospective association between the meal frequency, body mass index, and waist circumference; Participant characteristics at baseline: Spanish children; - Age: 10.1 (0.6)y; - Female: 51%; - Race and/or ethnicity: NR; - Socioeconomic position: 35% mothers with university degree; - Anthropometry: 31% with overweight/obesity; - Physical activity: ~3.0 (0.7) physical activity score (out of 5); - Smoking: NR; - TEI: NR; - Habitual diet at baseline: 58% eat 5 meals/d; 30% eat 4 meals/d; 12% eat ≤3 meals/d; Excluded from study or analysis: missing data; for incidence of excessive weight and abdominal obesity, children with outcome at baseline | Exposure: Number of eating occasions (≤3, 4, 5 meals/d); Assessment methods and timing:; - Children reported yes/no on whether they ate breakfast, mid-morning snack, lunch, afternoon snack, and dinner.; - At baseline; Outcomes and assessment methods:; - At baseline, 15mo follow-up; - Weight, height, and waist circumference were measured by trained personnel. BMI was calculated from height and weight, and overweight and obesity were defined based on IOTF cutoffs. Abdominal obesity was defined as a waist-to-height ratio ≥0.50 | [underlined: BMIz based on baseline meal frequency], Mean (95% CI); ≤3 meals/d: 0.78 (0.61, 0.95); 4 meals/d: 0.67 (0.61, 0.73); 5 meals/d: 0.62 (0.58, 0.66); p-trend=0.016; [underlined: Abdominal obesity based on baseline meal frequency], OR (95% CI); ≤3 meals/d: REF; 4 meals/d: 0.92 (0.32, 2.59); 5 meals/d: 0.38 (0.13, 1.11); p-trend: 0.028; [underlined: Waist-to-height ratio based on baseline meal frequency], Mean (95% CI); ≤3 meals/d: 0.471 (0.467, 0.475); 4 meals/d: 0.465 (0.463, 0.468); 5 meals/d: 0.463 (0.461, 0.465); p-trend<0.001; [underlined: Overweight/obesity based on baseline meal frequency], OR (95% CI); ≤3 meals/d: REF; 4 meals/d: 1.33 (0.48, 3.68); 5 meals/d: 0.54 (0.20, 1.45); p-trend: 0.035 | Model adjustments:; - TEI: no; - Key confounders: sex, age, socioeconomic position, anthropometry at baseline, physical activity; - Other: intervention group; school; adherence to Mediterranean diet; Limitations:; - Did not account for key confounders: race and/or ethnicity; - Exposure data only assessed at baseline leading to a concern that changes in exposure status occurred over f/u; - No information on non-completers; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; Instituto de Salud Carlos III FEDER; European Regional Development Fund
Ritchie, 2012^84^; PCS, NHLBI Growth and Health Study, U.S.; Analytic N=2,146; Study objective: To assess the prospective relation of an objective measure of eating frequency with adiposity in girls from ages 9–10 to 19–20y.; Participant characteristics at baseline: Black and White adolescent females; - Age: 9–10y; - Female: 100%; - Race and/or ethnicity: White: 49%; Black: 51%; - Socioeconomic position: 8.59 (3.43) maximum years of parental education by either parent; - Anthropometry: BMI 18.6 (3.8) kg/m^2^; - Physical activity: "sometimes" physically active; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: 4.96 (2.01) eating occasions per day; Excluded from study or analysis: not age within 2wk of 9–10y, black or white, living with parents or guardians with racial concordance, and parent or guardian providing information on the demographic characteristics; not missing data on any control variables | Exposure: Number of eating occasions (1–3, 3.1–4, 4.1–6, >6 times/d); Assessment methods and timing:; - 3d diet record; - At baseline (averaged over 2 visits at ages 9–11y); Outcomes and assessment methods:; - At baseline, 10y follow-up; - Height, weight, and waist circumference (WC) were measured by trained examiners. BMI was calculated from height and weight. | [underlined: Change in WC (cm) over 10y based on baseline eating frequency], Mean (SE); ALL; 1–3x/d: 12.49 (0.86); 3.1–4x/d: 11.93 (0.64); 4.1–6x/d: 11.62 (0.60); >6x/d: 10.26 (0.79) p=0.036; BLACK; Lower total eating frequency associated with greater increases in WC, p=0.010; WHITE; Lower total eating frequency associated with greater increases in WC, p=0.015; [underlined: Change in BMI (kg/m^2^) over 10y based on baseline eating frequency], Mean (SE); ALL; 1–3x/d: 7.83 (0.37); 3.1–4x/d: 7.35 (0.26); 4.1–6x/d: 7.28 (0.24); >6x/d: 6.54 (0.30) p=0.013; BLACK; Data NR; WHITE; Lower total eating frequency associated with greater increases in BMI, p=0.012 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, physical activity; - Other: dieting for weight loss, TV/video viewing; Limitations:; - Exposure data only assessed at baseline leading to a concern that changes in exposure status occurred over 10y f/u; - No information on non-completers; - No preregistered data analysis plan; - Beverages was not accounted for in exposure assessment; Funding:; USDA; NIH
Syrad, 2016^98^; PCS, Gemini twin cohort, UK; Analytic N=1,939; Study objective: To examine the relative contributions of meal size and frequency to weight gain; Participant characteristics at baseline: preschool children; - Age: 24.35 (1.02)mo; - Female: 52%; - Race and/or ethnicity: White: 96%; Non-White: 4%; - Socioeconomic position: 51% high maternal education, 49% low/intermediate; - Anthropometry: 17% overweight/obesity; - Physical activity: NR; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: NR; Excluded from study or analysis: missing data | Exposure: Number of eating occasions per day; Defined meals as eating occasions in which food was consumed at a single clock time (and drinks, if consumed at the same time); Assessment methods and timing:; - 3d diet record (2 weekdays and 1 weekend day); - At baseline (age 21mo); Outcomes and assessment methods:; - Every 3mo between age 2–5y; - Parents measured their child's height and weight. | [underlined: Weight gain (g/wk) between age 2–5y based on eating frequency at age 21mo], β (SE); 1.0 (0.3) p=0.001 | Model adjustments:; - TEI: no; - Key confounders: sex, age, anthropometry at baseline; - Other: meal size; Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position, physical activity; - Exposure data only assessed at baseline leading to a concern that changes in exposure status occurred over 3y follow-up; - High attrition rate/missing data; - Outcome was self-reported; - No preregistered data analysis plan; - Did not adjust for TEI; Funding:; NR
Taylor, 2017^99^; PCS, Secondary analysis of the Prevention of Overweight in Infancy intervention, New Zealand; Analytic N=371; Study objective: To determine whether eating frequency (meals and snacks) at 2 years of age is associated with past, current or subsequent BMI; Participant characteristics at baseline: preschool-aged children; - Age: 2y; - Female: 49%; - Race and/or ethnicity: New Zealand European and others: 89%; Asian: 5%; Maori: 6%; - Socioeconomic position: 61% maternal education university degress or higher; - Anthropometry: Birth weight: 3551g; - Physical activity: NR; - Smoking: 17% maternal smoking during pregnancy; - TEI: NR; - Habitual diet at baseline: 3.0 (0.7) meals/d; 2.6 (1.3) snacks/d; 5.6 (1.3) eating occasions per day; Excluded from study or analysis: missing data | Exposure: Number of eating occasions per day; Assessment methods and timing:; - 2 day food diary completed by parents in 5-min blocks. To qualify as separate eating occasion, the start of the next meal or snack had to be >15min after the end of the previous meal or snack (i.e., separated by at least four 5-min blocks). Mean total number of eating occasions per day was calculated as average from meals and snacks combined across the 2 days.; - At 2y; Outcomes and assessment methods:; - At 2y and 3.5y; - Height and weight were measured by study personnel and used to calculated BMI. BMI z-scores (BMIz) were calculated based on WHO reference data. | [underlined: Change in BMIz over 1.5y based on baseline eating frequency], β (95% CI); 0.02 (−0.03, 0.06), p=NS | Model adjustments:; - TEI: no; - Key confounders: sex, age, socioeconomic position, anthropometry at baseline; - Other: Intervention group; parity; maternal pre-pregnancy BMI; smoking during pregnancy; weeks of exclusive breastfeeding; birth weight; Limitations:; - Did not account for key confounders: race and/or ethnicity, physical activity; - Exposure was not well defined and was subject to measurement error; - Did not provide evidence as to whether the result was unbiased due to missing data; - No preregistered data analysis plan; - Did not adjust for TEI; Funding:; Health Research Council of New Zealand
Thompson, 2006^100^; PCS, U.S.; Analytic N=101; Study objective: To describe child and adolescent dietary patterns and to determine associations between childhood dietary pattern and longitudinal change in body mass index z-score among girls; Participant characteristics at baseline: 8–12yo girls; - Age: 9y; - Female: 100%; - Race and/or ethnicity: White: 74%; Other: 26%; - Socioeconomic position: paternal education: 19% no college, 22% college, 59% graduate; maternal education: 28% no college, 19% college, 53% graduate; 40% with parental income <$50k; - Anthropometry: 4% with BMI ≥85th percentile; - Physical activity: 51% more than peers, 40% same as peers, 9% less than peers; - Smoking: NR; - TEI: 1726 (1096–2817) kcal/d; - Habitual diet at baseline: 4.9 (2.9–8.9) dietary events per day; Excluded from study or analysis: missing dietary data; triceps skinfold thickness ≥85th percentile by age and sex; not in good health; post-menarche | Exposure: Eating frequency (0–3.9 times/day, 4.0–5.9 times/day, and ≥6.0 times/day on weekends, weekend days, and weekdays/weekend days combined); Dietary events (eating and drinking) were considered independent if they were separated by ≥15min.; Assessment methods and timing:; - 7d diet record of food and beverage items (excluding water); dietary events were classified based on time of day, frequency, and amount of energy consumed instead of traditional meal and snack classifications; - At baseline (8–12y), and ~6y follow-up (11–19y); Outcomes and assessment methods:; - At baseline (8–12y), and ~6y follow-up (11–19y); median follow-up was 6y (range 2–10y); - Height and weight were measured and used to calculate BMI. Age- and sex-specific BMI z-scores (BMIz) were computed based on CDC growth charts. | [underlined: Change in BMIz over ~6y follow-up by baseline eating frequency], Mean (SE); Weekdays and weekend days combined, Daily; ≥6.0 times/d: 0.55 (0.12), REF; 4.0–5.9 times/d: 0.24 (0.07), p=0.0280; 0.0–3.9 times/d: 0.38 (0.14), p=NS; Weekdays, Daily; ≥6.0 times/d: 0.60 (0.11), REF; 4.0–5.9 times/d: 0.19 (0.07), p=0.0024; 0.0–3.9 times/d: 0.50 (0.15), p=NS; Weekend days, Daily; ≥6.0 times/d: 0.43 (0.12), REF; 4.0–5.9 times/d: 0.28 (0.08), p=NS; 0.0–3.9 times/d: 0.33 (0.12), p=NS | Model adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, physical activity; - Other: parental BMI; time between baseline and follow-up; Limitations:; - Start of follow-up and exposure do not coincide; - No information on non-completers; - No preregistered data analysis plan; - Water was not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; NIH; CDC

a Abbreviations: ALT: alanine aminotransferase; AST: aspartate aminotransferase; AUD: Australian Dollar; β: beta coefficient; BMI: body mass index; BMIz: body mass index z-score; BP: blood pressure; CDC: Centers for Disease Control and Prevention; CI: confidence interval; cm: centimeter(s); d: day(s); DEXA: dual energy x-ray absorptiometry; FFQ: food frequency questionnaire; g: gram(s); GGT: gamma-glutamyl transferase; HbA1c: hemoglobin A1C; HOMA-IR: Homeostatic Model Assessment of Insulin Resistance; hr: hour(s); HR: hazard ratio; IOTF: International Obesity Task Force; IQR: interquartile range; kcal: kilocalorie(s); kg: kilogram(s); lb: pound(s); m: meter(s); MET: metabolic equivalent; min: minute(s); mm: millimeter(s); MVPA: moderate to vigorous physical activity; N/A: not applicable; NCC: nested case control study; NCI: National Cancer Institute; NHLBI: National Heart, Lung, and Blood Institute; NICHD; Eunice Kennedy Shriver National Institute of Child Health and Human Development; NIDDK: National Institute of Diabetes and Digestive and Kidney Diseases; NIH: National Institutes of Health; NISOC: nmol: nanomole; NR: not reported; NS: not significant; OR: odds ratio; PCS: prospective cohort study; Project EAT: Project Eating and Activity over Time; RCS: retrospective cohort study; REF: reference group; RMB: renminbi (Chinese yuan); RR: risk ratio; SD: standard deviation; SDS: standard deviation score; SE: standard error; SEP: socioeconomic position; SES: socioeconomic status; svg: serving(s); TAG: triacylglycerol; TEI: total energy intake; wk: week(s); x: time(s); y: year(s)

Table 32 Risk of bias for observational studies examining number of eating occasions in children and adolescents and growth, body composition, and risk of obesity^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Arenaza, 2020^86^ | HIGH | SOME CONCERNS | LOW | LOW | HIGH | LOW | LOW | HIGH
Bernabe-Ortiz, 2020^88^ | HIGH | SOME CONCERNS | SOME CONCERNS | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Evans, 2015^90^ | LOW* | HIGH | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Juton, 2023^94^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Ritchie, 2012^84^ | LOW* | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Syrad, 2016^98^ | HIGH | SOME CONCERNS | LOW | LOW | HIGH | SOME CONCERNS | SOME CONCERNS | HIGH
Taylor, 2017^99^ | HIGH | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Thompson, 2006^100^ | LOW* | SOME CONCERNS | SOME CONCERNS | LOW | HIGH | LOW | SOME CONCERNS | HIGH

a Possible ratings of low, moderate, serious, critical, or no information determined using the "Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)" tool (ROBINS-E Development Group ( Higgins J, Morgan R, Rooney A, Taylor K, Thayer K, Silva R, Lemeris C, Akl A, Arroyave W, Bateson T, Berkman N, Demers P, Forastiere F, Glenn B, Hróbjartsson A, Kirrane E, LaKind J, Luben T, Luben T, Luben T, Luben T, Luben T, Luben T, Luben T, Luben T, O'Connor A, Luben T, Savović J, Schubauer-Berigan M, Luben T, Luben T, Luben T, Luben T, Luben T, Luben T, Luben T, Luben T, Luben T, Luben T, Luben T, Luben T). Risk Of Bias In Nonrandomized Studies - of Exposure (ROBINS-E). Launch version, 1 June 2022. Available from: https://www.riskofbias.info/welcome/robins-e-tool. ) *Low risk of bias except for concerns about uncontrolled confounding.

Table 33 Evidence examining the relationship between number of eating occasions in adults and older adults and body composition and risk of obesity^a^

Study and Population Characteristics | Intervention, Comparator, and Outcome(s) | Results | Study Limitations
RANDOMIZED CONTROLLED TRIALS
Bachman, 2012^87^; RCT-Parallel, Lifestyle, Eating, and Activity Patterns (LEAP), U.S.; Baseline N=51, Analytic N=51 (Attrition: 0%); Study objective: To examine the effect of eating frequency on hunger, energy intake, and weight loss during a 6-month behavioral weight loss intervention; Participant characteristics at baseline: adults with overweight/obesity participating in a 6mo behavioral weight loss intervention; - Age: 51 (9.9)y; - Female: 58%; - Race and/or ethnicity: White: 94%; Black: 6%; Asian: 0%; American Indian: 0%; Other: 0%; non-Hispanic: 98%; - Socioeconomic position: Education: 8% high school, 4% vocational school, 31% some college, 31% college graduate, 26% graduate school; 78% married; 12% divorced/separated; - Anthropometry: BMI 35.5 kg/m^2^ (100% with overweight or obesity); - Physical activity: ~800 kcal/wk expended; - Smoking: NR; - TEI: ~2200 kcal/d; - Habitual diet at baseline: ~4 eating bouts/d (~2.8 meals, 1.2 snacks); Excluded from study or analysis: age <21 and >65y; BMI <27 and >45 kg/m^2^, reported a heart condition; chest pain or loss of consciousness during activity, unable to walk 2 blocks without stopping, major psychological disease; diabetes; recent weight loss or in a weight loss program; moving outside the area; pregnant, lactating, <6mo postpartum, or planned to become pregnant; unwilling to complete study meetings, assessments, or food diaries for duration of study | Intervention: 6 vs 3 meals per day (hypocaloric); 6 Meal Group (n=26): Instructions to “graze” by eating at least 100 kcal every 2–3hr + standard behavioral intervention for obesity for 6mo (~6 eating bouts/d at 3 and 6mo, 3 meals and 3 snacks); 3 Meal Group (n=25): Instructions to eat 3 meals/d + standard behavioral intervention for obesity for 6mo (~3 eating bouts/d at 3 and 6mo, all 3 meals); Participants defined meals and snacks, which were only counted if at least 25kcal were consumed. All foods and beverages eaten within ½hr of the start of a meal/snack were counted as a single eating bout. Eating frequency equaled the number of meals, snacks, and total eating bouts (meals + snacks) reported in the food records.; Duration: 6mo; Compliance: Based on percent of self-monitoring diaries turned in and attendance for each participant. NS difference between conditions for self-monitoring, attendance, and retention at 3 or 6 month assessments.; Outcomes and assessment methods:; - At baseline, 3mo, and 6mo; - Height and weight: measured by study staff; used to calculate BMI (kg/m^2^); - Body fat (%) and fat-free mass (kg): assessed by bioelectrical impedance analysis | [underlined: Body fat (%)], Mean (SD):; Within group: 0mo, 3mo, 6mo, p<0.001; 3 Meals: 41.3 (7.0), 37.6 (10.5), 32.3 (9.3), p<0.001; Grazing: 40.2 (8.5), 35.7 (9.2), 33.1 (10.2), p<0.001; Between groups: p=NS at 0, 3, 6mo; [underlined: Fat-free mass (kg)], Mean (SD):; Within group: 0mo, 3mo, 6mo; 3 Meals: 58.8 (12.9), 56.7 (14.5), 57.9 (14.2), p<0.001; Grazing: 60.8 (15.2), 60.0 (14.5), 58.8 (12.6), p<0.001; Between groups: p=NS at 0, 3, 6mo; [underlined: BMI (kg/m^2^)], Mean (SD); Within group: 0mo, 3mo, 6mo, p<0.001 3; Meals: 35.7 (4.9), 31.5 (4.1), 29.8 (4.4), p<0.001; Grazing: 36.3 (5.4), 32.5 (5.1), 31.3 (5.3), p<0.001; Between groups: p=NS at 0, 3, 6mo | Model adjustments:; - TEI: yes; Limitations:; - Water was not accounted for in exposure assessment; Funding:; American Heart Association
Forslund, 2008^89^; RCT-Parallel, Sweden; Baseline N=140, Analytic N=93 (Attrition: 34%); Study objective: To examine the effect of two different recommended eating frequencies on 1-year weight loss; Participant characteristics at baseline: adults with obesity; - Age: ~41 (11)y; - Female: 71%; - Race and/or ethnicity: NR; - Socioeconomic position: NR; - Anthropometry: All with BMI >30 kg/m^2^; - Physical activity: NR; - Smoking: NR; - TEI: ~2700 kcal/d; - Habitual diet at baseline: NR; Excluded from study or analysis: aged <18 or >60y; BMI <30 kg/m^2^; participants reporting previous obesity surgery, anti-obesity drug treatment the last year, drug or insulin-treated diabetes, hypothyroidism, severe psychiatric disorder, bulimia, drug or alcohol abuse | Intervention: 6 vs 3 meals per day (hypocaloric); 6 meals a day (6M, n=44): daily energy intake divided into breakfast (20%), lunch (25%), dinner (25%) and 3 snacks (10% each).; 3 meals a day (3M, n=46): daily energy intake divided in breakfast (30%), lunch (35%) and dinner (35%). No snacks with the exception of limited fruit intake and calorie-free drinks.; Duration: 1yr; Compliance: Measured using repeated telephone intervals at 6 time periods during the 1yr intervention; Outcomes and assessment methods:; - At baseline, 1yr; - Weight measured by study staff | [underlined: Weight loss after 1yr (kg)], Mean (SD); 3M: −4.1 (6.1); 6M: −5.9 (9.4) p=0.31; Completers only: p=0.34; All participants using LOCF: p=0.35 | Limitations:; - Concerns with deviations from intended intervention; - High rates of attrition, and unclear how missing data impacted results; - Not sufficiently powered; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; Funding:; Västra Götalandsregionen
Grangeiro, 2021^92^; RCT-Parallel, Brazil; Baseline N=47, Analytic N=40 (Attrition: 15%); Study objective: To examine the effect of different meal frequencies on weight loss, body composition, blood glucose, plasma lipids, active ghrelin, and energy expenditure outcomes among women with obesity who had enrolled in a weight loss intervention.; Participant characteristics at baseline: women with obesity enrolled in a weight loss intervention; - Age: Mean ~30y; - Female: 100%; - Race and/or ethnicity: NR; - Socioeconomic position: NR; - Anthropometry: BMI ~35 kg/m^2^; - Physical activity: Asked to maintain physical activity during intervention; - Smoking: All nonsmokers; - TEI: ~1900 kcal/d; - Habitual diet at baseline: NR; Excluded from study or analysis: BMI <30 and ≥50 kg/m^2^, aged <20 or >45y, menopausal, smokers, with restricted diets, with recent changes in body weight (±3 kg in the previous three months), undergone bariatric surgery, athletes, users of medication or supplements for weight control, people diagnosed with acute or chronic disease, (e.g., decompensated hypothyroidism, diabetes, respiratory complications, cancer, inflammatory bowel disease, liver and severe kidney diseases, and heart disease), dyslipidemia, illiterate, those with severe food compulsion at baseline (based on Binge Eating Scale) | Intervention: 6 vs 3 meals a day (hypocaloric); The 6-meal group was a hypocaloric diet divided into breakfast (15% TEE), snack (5–10% TEE), lunch (25% TEE), snack (5–10% TEE), dinner (25% TEE) and evening snack (5–10% TEE).; The 3-meal group was a hypocaloric diet divided into breakfast (20–25% TEE), lunch (35–40% TEE), and dinner (35–40% TEE).; The diets had the same macronutrient distribution. Diets were reduced 500–1000 kcal/d to obtain body weight reduction of 2–4 kg/mo. Breakfast, lunch and dinner were defined to provide more than 15% of the TEE and the snacks provided less than 15% of the TEE.; Duration: 12wk; Compliance: Self-reported dietary adherence: NS difference between groups; percentage (~75%) remained similar throughout intervention period; Outcomes and assessment methods:; - At baseline, 12wk; - Weight, height, and waist circumference (WC) measured by study staff; - BMI calculated from height and weight; - Fat mass (FM) and fat-free mass (FFM) estimated using bioelectrical impedance analysis | [underlined: WC (cm)], Marginal mean (SD); Within group: baseline, 12wk; 6-meal: 97.20 (1.95), 93.62 (2.31), p=0.227; 3-meal: 101.3 (1.95), 96.46 (2.06), p=0.046; Between groups: p=0.487 at baseline p=0.826 at 12wk; [underlined: FFM (kg)], Marginal mean (SD); Within group: baseline, 12wk; 6-meal: 48.72 (0.84), 48.80 (1.00), p=0.999; 3-meal: 48.36 (0.86), 48.96 (0.88), p=0.836; Between groups: p=0.989 at baseline p=0.999 at 12wk; [underlined: FM (kg)], Marginal mean (SD); Within group: baseline, 12wk; 6-meal: 42.13 (0.94), 39.99 (1.19), p=0.189; 3-meal: 41.66 (0.99), 42.51 (1.03), p=0.825; Between groups: p=0.982 at baseline p=0.452 at 12wk; [underlined: Weight (kg)], Marginal mean (SD); Within group: baseline, 12wk; 6-meal: 90.85 (1.26), 88.71 (1.54), p=0.361; 3-meal: 90.07 (1.31), 91.51 (1.35), p=0.637; Between groups: p=0.970 at baseline p=0.580 at 12wk; [underlined: BMI (kg/m^2^)], Marginal mean (SD); Within group: baseline, 12wk; 6-meal: 34.95 (0.60), 33.99 (0.69), p=0.221; 3-meal: 34.30 (0.61), 34.60 (0.61), p=0.918; Between groups: p=0.867 at baseline p=0.924 at 12wk; [underlined: Change in WC (cm) from baseline to 12wk], Marginal mean (SD); 6-meal: 3.30 (1.37); 3-meal: 5.23 (1.26) p=0.427; [underlined: Change in FFM (kg) from baseline to 12wk], Marginal mean (SD); 6-meal: 0.69 (0.59); 3-meal: 0.37 (0.54) p=0.758; [underlined: Change in FM (kg) from baseline to 12wk], Marginal mean (SD); 6-meal: 4.05 (0.73); 3-meal: 1.64 (0.67) p=0.071; [underlined: Change in weight (kg) from baseline to 12wk], Marginal mean (SD); 6-meal: 4.75 (0.91); 3-meal: 2.01 (0.84) p=0.097; [underlined: Change in BMI (kg/m^2^) from baseline to 12wk], Marginal mean (SD); 6-meal: 1.83 (0.34); 3-meal: 0.75 (0.32) p=0.087 | Limitations:; - Methods for concealment NR; - Concerns with deviations from intended intervention; - Differences in attrition; - Water/Beverages were not accounted for in exposure assessment; Funding:; Coordenação de Aperfeiçoamento de Pessoal de Nível Superior (CAPES)
Yildiran, 2019^101^; RCT-Parallel, Turkey; Baseline N=65, Analytic N=47 (Attrition: 28%); Study objective: To estimate the effects of meal frequency (three meals/day or six meals/day) in a three-month medical nutrition therapy on weight loss, body composition, fasting serum glucose, insulin levels, and lipid profiles in overweight or obese females between 20 and 49 years old.; Participant characteristics at baseline: females with overweight or obesity; - Age: 35 (4)y; - Female: 100%; - Race and/or ethnicity: NR; - Socioeconomic position: NR; - Anthropometry: BMI ~35 (5) kg/m^2^; - Physical activity: NR; - Smoking: NR; - TEI: ~1525 (118) kcal/d; - Habitual diet at baseline: NR; Excluded from study or analysis: male; aged <20 or >49y; BMI <27 kg/m^2^; chronic disease (not including hyperlipidemia) or health problems; missing weekly data; did not follow planned medical nutrition therapy; menstrual irregularities | Intervention: 6 vs 3 eating occasions (hypocaloric); 6 meals a day (6M, n=24): 6 meals a day (breakfast, lunch, dinner, and three snacks) 3 meals a day (3M, n=23): 3 meals a day (breakfast, lunch, dinner); All participants were on a weight loss diet.; Duration: 3mo; Compliance: weekly 24hr diet records to check adherence; Outcomes and assessment methods:; - At baseline, 3mo follow-up; - Weight, height, and waist circumference (WC) measured by study staff; - BMI calculated from height and weight Fat mass (FM) and fat-free mass (FFM) estimated using bioelectrical impedance analysis | [underlined: FM (kg)]; Within group, Mean (SD): baseline, 3mo; 3M: 39.0 (8.2), 33.3 (7.9), p=0.000; 6M: 41.4 (10.1), 36.1 (9.1), p=0.000; Between group, Mean difference (SD): over 3mo; 3M: 5.69 (1.99); 6M: 5.22 (2.58) p=0.630; [underlined: FFM (kg)]; Within group, Mean (SD): baseline, 3mo; 3M: 47.2 (4.8), 46.7 (3.5), p=1.000; 6M: 54.1 (5.3), 53.7 (5.1), p=1.000; Between group, Mean difference (SD): over 3mo; 3M: 0.44 (1.89); 6M: 0.40 (3.37) p=0.518; [underlined: WC (cm)]; Within group, Mean (SD): baseline, 3mo; No Snacking: 101.0 (10.7), 93.2 (9.3), p=0.001; Snacking: 102.0 (7.8), 95.9 (7.9), p=0.000; Between group, Mean difference (SD): over 3mo No; Snacking: 7.73 (4.47); Snacking: 6.17 (3.32) p=0.455; [underlined: Weight (kg)]; Within group, Mean (SD): baseline, 3mo; 3M: 86.2 (10.5), 80.0 (9.5), p=0.000; 6M: 94.8 (14.6), 89.8 (13.5), p=0.000; Between group, Mean difference (SD): over 3mo; 3M: 5.91 (2.64); 6M: 4.97 (2.70) p=0.411; [underlined: BMI (kg/m^2^)]; Within group, Mean (SD): baseline, 3mo; 3M: 35.2 (4.9), 32.7 (4.3), p=0.000; 6M: 34.2 (4.6), 32.6 (4.4), p=0.001; Between group, Mean difference (SD): over 3mo; 3M: 2.37 (1.22); 6M: 1.70 (0.97) p=0.157 | Model adjustments:; - TEI: yes; Limitations:; - Methods for randomization and concealment NR; - No power calculation; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; - Did not describe impacts of missing outcome data; Funding:; NR
Zargaran, 2014^102^; RCT-Parallel, Iran; Baseline N=90, Analytic N=84 (Attrition: 7%); Study objective: To assess the effects of daily energy intake in 6 isocaloric meals in comparison to the current traditional diet (with 3 meals and 2 small snacks per day) on weight, lipid profiles, leptin, and adiponectin for 3 months; Participant characteristics at baseline: adults with overweight; - Age: 37 (10)y; - Female: 80%; - Race and/or ethnicity: NR; - Socioeconomic position: 61% with academic degrees; 55% employed; 70% married; - Anthropometry: BMI 30 (5) kg/m^2^; - Physical activity: NR; - Smoking: All nonsmokers; - TEI: NR; - Habitual diet at baseline: "most" ate 3 meals and 2 snacks a day; Excluded from study or analysis: aged <20 or >60y; taking cholesterol-lowering drugs; on lipid-lowering or weight control diets; conditions causing secondary hypercholesterolemia (e.g., hyperthyroidism, pregnancy); working night shifts; smoking; suffering from chronic diseases (e.g., cancer, renal failure, heart failure) | Intervention: 6 isocaloric meals vs usual diet (hypocaloric); 6 meals (n=41): 6 isocaloric meals, one meal every 3hr; Control (n=43): usual diet, which was usually 5 meals (3 main meals and 2 snacks); All participants followed a weight loss diet.; Duration: 3mo; Compliance: four 24h dietary recalls throughout intervention to assess adherence; Outcomes and assessment methods:; - At baseline, 3mo follow-up; - Weight and height were measured and used to calculate BMI. | [underlined: BMI (kg/m^2^)], Mean (SD); Within group: Baseline, 3mo; Control: 30.3 (4.7), 29.5 (4.3), p<0.001; 6 Meals: 30.9 (5.2), 28.9 (4.9), p<0.001; Between group difference from baseline to 3mo Control: 0.7 (1.1); 6 Meals: 1.9 (0.9) p<0.001 | Limitations:; - Methods for randomization and concealment NR; - No power calculation; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; Funding:; Shiraz University of Medical Sciences
PROSPECTIVE COHORT STUDIES
Georgiopoulos, 2017^91^; PCS, Greece; Analytic N=115; Study objective: To investigate potential associations between EF and ultrasonographically measured regional fat layers in apparently healthy individuals under a longitudinal study design over a follow-up period of 5-years; Participant characteristics at baseline: healthy adults; - Age: 54 (9.1)y; - Female: 61%; - Race and/or ethnicity: NR; - Socioeconomic position: NR; - Anthropometry: BMI 26.2 (5.2) kg/m^2^; - Physical activity: 29% report moderate intensity ≥150 min/wk; - Smoking: 36% current; - TEI: ~1823 kcal/d; - Habitual diet at baseline: Median (IQR), 5 (4.3–6) eating occasions/day. Median selected as REF.; Excluded from study or analysis: history of coronary artery disease, diabetes, liver or endocrine diseases, autoimmune disease, cancer, or active infection; alcohol consumption ≥30g/d; dieting at baseline | Exposure: ≤5 vs >5 eating occasions/day (also examined as quartiles of eating occasions per day); An eating occasion was defined as any eating occasion when food or drink was consumed, including consumption of alcoholic drinks, soft drinks, kcal-free meals or coffees and teas eaten in the absence of food (i.e., a cup of coffee with milk and sugar, or a coke or diet soda). Multiple eating episodes recorded within ≤15min were counted as a single eating occasion.; Assessment methods and timing:; - Eating frequency was assessed as the mean of eating episodes over 3d, which was based on dietary records on 2 consecutive weekdays and 1 weekend day.; - At baseline; Outcomes and assessment methods:; - At baseline, 5y follow-up; - Weight and height were measured and used to calculate BMI.; - Waist circumference was measured. Subcutaneous fat (Smin) and pre-peritoneal fat (Pmax) were measured using B-mode ultrasonography to assess regional adiposity. The ratio of Smin to Pmax was calculated and defined as the abdominal fat index (AFI). | [underlined: ≤5 (REF) vs >5 eating occasions per day]; [underlined: Waist circumference (cm)]: β=−0.068, p=0.418; [underlined: Smin (mm)]: β=0.247, p=0.144; [underlined: Pmax (mm)] : β=−0.452, p=0.006; [underlined: AFI]: β=0.563, p=0.003; Polynomial trend analysis of quartiles of eating occasions:; Pmax (mm): quadratic contrast=0.019, p=0.761; AFI: quadratic contrast=−0.107, p=0.126; Quadratic term in regression:; Pmax (mm): β =−0.001, p=0.524 AFI: β =−0.001, p=0.864; [underlined: BMI (kg/m^2^)]; β=−0.337, p=0.078 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, anthropometry at baseline (except in analysis of BMI), physical activity (for AFI and Pmax), smoking; - Other: HbA1c; Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position; - Exposure data only assessed at baseline leading to a concern that changes in exposure status occurred over 5y f/u; - No preregistered data analysis plan; - Water was not accounted for in exposure assessment; Funding:; NR
LaRose, 2019^32^; PCS, secondary analysis of Study of Novel Approaches to Weight Gain Prevention (SNAP) trial, U.S.; Analytic N=500; Study objective: To examine changes in key dietary outcomes within the SNAP Trial and explore whether improvements in these dietary behaviors were associated with more favorable weight trajectories over 2 years of follow-up.; Participant characteristics at baseline: adults aged 18–35y; - Age: 28.2 (4.4)y; - Female: 78%; - Race and/or ethnicity: Non-Hispanic White: 73%; African-American: 11%; Asian/Pacific Islander: 4%; Multiple/Refusal: 4%; Hispanic: 8% Socioeconomic position: 20% not college graduate; 80% college graduate; 63% employed full-time; 29% full-time student; 9% other; - Anthropometry: BMI 25.4 (2.6) kg/m^2^ (50% with overweight); - Physical activity: NR; - Smoking: NR; - TEI: 1663 (611) kcal/d; - Habitual diet at baseline: 4.7 (2.3) eating occasions/d; 5.6 (1.8) breakfast/wk; 48% eat breakfast daily; Excluded from study or analysis: age <18 or >35 y; BMI <21 or >30 kg/m^2^; major medical comorbidities; recent weight lost ≥10 lbs; current or planned pregnancy; no internet access; non-English speaking | Exposure: Number of eating occasions (times/d); Assessment methods and timing:; - Eating pattern questionnaire items assessed eating frequency over the past 30 days (exact question NR); - At baseline, 2y follow-up; Outcomes and assessment methods:; - At baseline, 2y follow-up; - Weight measured by trained research staff | [underlined: Change in weight from baseline to 4mo by change in number of eating occasions], Partial correlation; −0.02, p=0.70; [underlined: Change in weight from baseline to 2y by change in number of eating occasions], Partial correlation; −0.03, p=0.46 | Model adjustments:; - TEI: no; - Key confounders: anthropometry at baseline; - Other: trial group assignment; Limitations:; - Did not account for key confounders: sex, age, race and/or ethnicity, socioeconomic position, physical activity, smoking; - Exposure assessment method not validated; - Post-exposure interventions may have been influenced by prior exposure during f/u; - No information on non-completers; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; - Unclear if TEI was adjusted for; Funding:; NHLBI
Larsen, 2019^80^; PCS, Danish Monitoring Trends and Determinants in Cardiovascular Disease (MONICA) study, Denmark; Analytic N=2,124; Study objective: To examine the associations between eating frequency and 6-y changes in BMI, fat mass, fat-free mass, body fat percentage, and waist circumference.; Participant characteristics at baseline: middle-aged adults; - Age: 46 (36–66)y; - Female: 49%; - Race and/or ethnicity: NR Socioeconomic position: 30% ≤ primary level education; - Anthropometry: BMI 24 (20–32) kg/m^2^; - Physical activity: 23% inactive/sedentary; - Smoking: 50% never; - TEI: NR; - Habitual diet at baseline: Eats 4 (2, 6) times/d; 3 (2, 4) meals per day and 1 (0, 3) snacks per day; Excluded from study or analysis: missing data on eating frequency, adiposity measures, or covariates; prevalent cancer, cardiovascular disease, self-reported diabetes prior to health exam | Exposure: Total eating frequency (times/d); Assessment methods and timing:; - Participants completed a survey and reported how many meals they ate during the day and how often they snacked between meals.; - At T1 (1982–1983), and T2 (1987–1988); Outcomes and assessment methods:; - At T1 (1982–1983), T2 (1987–1988), and T3 (1993–1994); - Height, weight, and waist circumference (WC) were measured. Body fat percentage (BF%) was measured using bioelectric impedance. BMI, fat-mass index (FMI), and fat-free mass index (FFMI) were calculated. | [underlined: 6y change in FMI (kg/m^2^) from T2-T3], β (95% CI); Based on total eating frequency at T2; 0.01 (−0.03, 0.05), p=0.56; Based on 5yΔ in total eating frequency (T1-T2); 0.03 (−0.02, 0.07), p=0.21; [underlined: 6y change in FFMI (kg/m^2^) from T2-T3], β (95% CI); Based on total eating frequency at T2; −0.01 (−0.03, 0.00), p=0.12; Based on 5yΔ in total eating frequency (T1-T2); −0.01 (−0.03, 0.01), p=0.41; [underlined: 6y change in BF% from T2-T3], β (95% CI); Based on total eating frequency at T2; 0.05 (−0.04, 0.14), p=0.26; Based on 5yΔ in total eating frequency (T1-T2); 0.08 (−0.02, 0.18), p=0.09; [underlined: 6y change in WC (cm) from T2-T3], β (95% CI); Based on total eating frequency at T2; −0.03 (−0.23, 0.17), p=0.74; Based on 5yΔ in total eating frequency (T1-T2); 0.01 (−0.20, 0.23), p=0.90; Among subsample (n=314) with TEI: p=NS for FMI, FFMI, BF%, and WC; p=NS for effect modification by gender or obesity status; [underlined: 6y change in BMI (kg/m^2^) from T2-T3], β (95% CI); Based on total eating frequency at T2; 0.00 (−0.05, 0.05), p=0.99; Based on 5yΔ in total eating frequency (T1-T2); 0.02 (−0.03, 0.08), p=0.45; Among subsample (n=314) with TEI: p=NS for BMI; p=NS for effect modification by gender or obesity status | Model adjustments:; - TEI: yes, in a subsample of 314 participants; - Key confounders: sex, age, socioeconomic position, anthropometry at baseline, physical activity, smoking; - Other: alcohol intake; menopausal status for women; height (for WC); baseline intake of snacks or meals; Limitations:; - Did not account for key confounders: race and/or ethnicity; - Exposure assessment method not validated; - High attrition rate/missing data; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; - Did not adjust for TEI in full sample; Funding:; No external funding
Makarem, 2020^96^; PCS, U.S.; Analytic N=116; Study objective: To investigate cross-sectional and prospective associations of habitual nightly fasting duration, timing of the first and last eating occasions, and eating frequency with overall cardiovascular health and clinically relevant cardiometabolic risk factors in a community-based sample of US women.; Participant characteristics at baseline: women aged 20–64y; missing 1wk electronic food record or HbA1c at baseline and 1y follow-up; - Age: 33 (12)y; - Female: 100%; - Race and/or ethnicity: Racial/ethnic minority: 78%; Hispanic: 45%; - Socioeconomic position: 66% ≤college education; 58% with health insurance; - Anthropometry: BMI 25.7 (5.4) kg/m^2^; - Physical activity: 4.1 (5.3) hr/d of MVPA; - Smoking: 7% current; - TEI: NR; - Habitual diet at baseline: 3.9 (1.1) eating occasions/d; Excluded from study or analysis: aged >20 or >76y; pregnant | Exposure: Number of eating occasions per day (continuous); An eating occasion was defined as consuming ≥25 kcal; Assessment methods and timing:; - Electronic food record of 7 consecutive days was used to estimate average eating frequency based on the number of eating occasions on each reported day; - At baseline; Outcomes and assessment methods:; - At baseline, 1y follow-up; - Height, weight, and waist circumference were measured at clinic visit. Height and weight were used to calculate BMI. | [underlined: Waist circumference (in) at 1y based on eating frequency at baseline], β (SE); −0.27 (0.46), p=0.563; [underlined: BMI (kg/m^2^) at 1y based on eating frequency at baseline], β (SE); −0.79 (0.53), p=0.156 | Model adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, physical activity; - Other: none; Limitations:; - Did not account for key confounders: smoking; - Exposure data only assessed at baseline leading to a concern that changes in exposure status occurred over 1y f/u; - No preregistered data analysis plan; - Water was not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; AHA
Malaeb, 2020^97^; PCS, Secondary analysis of "See Food" feasibility trial, U.S.; Analytic N=20; Study objective: To examine time-restricted eating intervention-related alteration of eating patterns over a 12-week period, using a smartphone-based application centered on food pictures with textual option documentation, in metabolically healthy adults with overweight or obesity; Participant characteristics at baseline: metabolically healthy adults with overweight or obesity; - Age: 45.5 (12.1)y; - Female: 85%; - Race and/or ethnicity: White: 85%; Black: 15%; - Socioeconomic position: NR; - Anthropometry: BMI 34.1 (7.5) kg/m^2^; - Physical activity: NR; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: NR; Excluded from study or analysis: aged <18 or >65y; BMI <25 kg/m^2^; unstable sleep or work schedule; did not own a smartphone | Exposure: Number of eating occasions per day (continuous); An eating occasion was any occasion where any food or beverage (other than water or medicine) was ingested; and eating occasion was considered distinct if it occurred >15min apart from another eating occasion.; Participants were in 2 groups: a time-restricted eating (TRE) group vs a non-TRE group. The TRE group was counseled to self-select and maintain a daily 8h eating window during intervention.; Assessment methods and timing:; - Eating occasions were capture using mobile food records over 14d periods; - At baseline, 12wk (post intervention); Outcomes and assessment methods:; - At baseline, 12wk (post intervention); - Weight was measured | [underlined: Absolute weight loss (units NR) over 12wk based on change in number of eating occasions over 12wk]; TRE group: r=0.009, p=0.98; Non-TRE group: r=0.269, p=0.48; [underlined: Percent weight loss over 12wk based on change in number of eating occasions over 12wk]; TRE group: r=0.068, p=0.84; Non-TRE group: r=0.375, p=0.32 | Model adjustments:; - TEI: no; - Key confounders: sex, age, anthropometry at baseline; - Other: treatment arm; Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position, physical activity, smoking; - Water was not accounted for in exposure assessment; - Did not adjust for TEI; - Data was collected as part of a multi-component RCT, and it is not clear whether the authors isolated eating frequency as a variable; Funding:; Healthy Foods Healthy Lives program; NIH
Martinez, 2021^42^; PCS, Mexican Teachers’ Cohort, Mexico; Analytic N=65,099; Study objective: To evaluate the association between breakfast frequency and weight change in a well-established prospective cohort of middle-aged Mexican women.; Participant characteristics at baseline: middle-age Mexican women; - Age: 42.5 (7.1)y; - Female: 100%; - Race and/or ethnicity: 7% indigenous language/dialect (likely majority Mexican); - Socioeconomic position: 74% Bachelors degree or higher; 26% lower SES, 33% middle SES, 41% upper SES; All teachers; - Anthropometry: BMI 27 (4) kg/m^2^; - Physical activity: ~32 (29) METs hr/wk; - Smoking: 75% never; 15% former; 10% current; - TEI: ~1800 (600) kcal/d; - Habitual diet at baseline: 25% consume breakfast daily; Excluded from study or analysis: women who did not give information regarding the main exposure or outcome, breakfast frequency, and incomplete self-reported body weight; cancer at baseline; being pregnant at the time of any questionnaire; those who did not respond to ≥70 items of FFQ; those with energy intake <500 or >3500 kcal/d | Exposure: Frequency of meals (1–2, 3–4, ≥5 meals/d); Assessment methods and timing:; - “How many days a week do you have a solid breakfast (in addition to coffee, juice, milk, or tea)?” and "On average, how many meals per day do you eat (taking into account food between meals)?”; - At baseline; Outcomes and assessment methods:; - At baseline (2006–2008), and ~3y follow-up (2011); - Weight was self-reported | [underlined: Change in weight over 3y], PR (95% CI); 1–2 meals/d: −0.06 (−0.15, 0.04); 3–4 meals/d: REF; ≥5 meals/d: 0.24 (0.12, 0.37); p-trend<0.0001; [underlined: Weight gain ≥5kg over 3y], PR (95% CI); 1–2 meals/d: 0.99 (0.95, 1.03); 3–4 meals/d: REF; ≥5 meals/d: 1.16 (1.10, 1.22); p-trend<0.0001 | Model adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, physical activity, smoking; - Other: parity; use of contraceptive hormones; menopause status; sleep; meals aways from home; scores of diet patterns (fruit and vegetables, Western and Modern Mexican); Limitations:; - Exposure data only assessed at baseline leading to a concern that changes in exposure status occurred over 3y f/u; - High attrition rate/missing data; - Weight was self-reported; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; American Institute for Cancer Research; CONACyT
Megson, 2017^43^; PCS, secondary analysis of a weight loss trial, U.S.; Analytic N=211; Study objective: To examine the association between breakfast eating and eating frequency on BMI and weight loss outcomes among adults enrolled in a weight loss intervention.; Participant characteristics at baseline: adults with overweight or obesity; - Age: 47.3 (11.0)y; - Female: 83%; - Race and/or ethnicity: Non-Hispanic White: 87%; - Socioeconomic position: 92% college educated; - Anthropometry: BMI 34.2 (6.9) kg/m^2^; - Physical activity: NR; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: Eat breakfast 5.6 (2.0) days/wk; Ate meals and snacks 5.0 (2.7) meals and snacks per day (range 1–30); Excluded from study or analysis: age <18 or >70y; BMI <25 kg/m^2^; current or planned pregnancy or serious medical condition for which weight loss and regular exercise would be unsafe; no Internet access; non-English speaking | Exposure: Number of eating occasions (continuous; number of meals and snacks per day); also examined categorically (increased, decreased, or had no change in eating frequency from pre- to post-treatment); Assessment methods and timing:; - ‘‘On average, how many days per week do you eat breakfast?’’ Response options ranged from zero to seven.; - ‘‘Counting all meals and any snacks you may have, how many times a day do you usually eat?"; At baseline and 3mo follow-up (pre- and post-intervention); Outcomes and assessment methods:; - At baseline and 3mo follow-up (pre- and post-intervention); - Weight measured and used to compute overall weight loss and percentages of participants who achieved a 5% weight loss. | [underlined: Percent weight loss over 3mo by baseline eating frequency]; β=0.04, p=0.58; [underlined: 5% weight loss over 3mo by baseline eating frequency]; β=0.04, p=0.45; [underlined: Percent weight loss over 3mo by change in eating frequency (increase, decrease, no change) over 3mo], Mean (SD); Ate ≤3 times/d at baseline; Increase: 5.0 (5.9); No Change: 2.1 (3.7) p=0.21; Ate ≥6 times/d at baseline; Decrease: 4.0 (5.4); No Change: 3.5 (4.9); Increase: 2.3 (3.7) p=0.87; [underlined: Achieving 5% weight loss at 3mo by change in eating frequency (increase, decrease, no change) over 3mo]; Decrease: 46.4% No Change: 40.0% Increase: 25.0% p=0.42 | Model adjustments:; - TEI: no; - Key confounders: age, anthropometry at baseline; - Other: treatment arm; Limitations:; - Did not account for key confounders: sex, race and/or ethnicity, socioeconomic position, physical activity, smoking; - Exposure assessment method not validated; - Did not describe or account for the impacts of missing data; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; NR
van der Heijden, 2007^67^; PCS, Health Professionals Follow-up Study, U.S.; Analytic N=20,064; Study objective: To investigate the association between breakfast consumption and weight gain in an adult male population over a 10-year period.; Participant characteristics at baseline: middle-age and older men; - Age: ~57y; - Female: 0%; - Race and/or ethnicity: NR; - Socioeconomic position: All health professionals; ~77% work full-time; - Anthropometry: BMI ~25.6 kg/m^2^; - Physical activity: ~38 MET hr/wk; ~21% any weight training; - Smoking: ~6% current; - TEI: NR; - Habitual diet at baseline: 17% skip breakfast; Excluded from study or analysis: missing values for breakfast skipping or BMI at baseline; implausible energy intakes (>4200 or <800 kcal/d); >70 blank items on FFQ; history of diabetes, CVD, or cancer (except non-melanoma skin cancer) at baseline; died during follow-up or missing values for BMI at follow-up | Exposure: Number of eating occasions (3, 4, ≥5 times/day); Assessment methods and timing:; - “Please indicate the times of day that you usually eat.” The participants could mark all of the predefined answer categories that applied (before breakfast, breakfast, between breakfast and lunch, lunch, between lunch and dinner, dinner, between dinner and bedtime, and after going to bed).; - At baseline (1992); Outcomes and assessment methods:; - At baseline (1992), biennially until 2002; - Weight was self-reported. Substantial weight gain was defined as weight gain of ≥5 kg. | [underlined: 5kg weight gain over 10y follow-up], HR (95% CI); meals/d: REF; meals/d: 1.07 (1.02, 1.14); ≥5 meals/d: 1.15 (1.06, 1.25); p-trend<0.001 | Model adjustments:; - TEI: no; - Key confounders: sex, age, socioeconomic position, anthropometry at baseline, physical activity, smoking; - Other: alcohol intake; Limitations:; - Did not account for key confounders: race and/or ethnicity; - Exposure data only assessed at baseline leading to a concern that changes in exposure status occurred over 10y f/u; - High attrition rate; - Weight was self-reported; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; NIH

a Abbreviations: AHA: American Heart Association; ALT: alanine aminotransferase; AST: aspartate aminotransferase; AUD: Australian Dollar; β: beta coefficient; BMI: body mass index; BMIz: body mass index z-score; BP: blood pressure; CDC: Centers for Disease Control and Prevention; CI: confidence interval; cm: centimeter(s); d: day(s); DEXA: dual energy x-ray absorptiometry; FFQ: food frequency questionnaire; g: gram(s); GGT: gamma-glutamyl transferase; HbA1c: hemoglobin A1C; HOMA-IR: Homeostatic Model Assessment of Insulin Resistance; hr: hour(s); HR: hazard ratio; IOTF: International Obesity Task Force; IQR: interquartile range; kcal: kilocalorie(s); kg: kilogram(s); lb: pound(s); m: meter(s); MET: metabolic equivalent; min: minute(s); mm: millimeter(s); MVPA: moderate to vigorous physical activity; N/A: not applicable; NCC: nested case control study; NCI: National Cancer Institute; NHLBI: National Heart, Lung, and Blood Institute; NICHD; Eunice Kennedy Shriver National Institute of Child Health and Human Development; NIDDK: National Institute of Diabetes and Digestive and Kidney Diseases; NIH: National Institutes of Health; NISOC: nmol: nanomole; NR: not reported; NS: not significant; OR: odds ratio; PCS: prospective cohort study; Project EAT: Project Eating and Activity over Time; RCS: retrospective cohort study; REF: reference group; RMB: renminbi (Chinese yuan); RR: risk ratio; SD: standard deviation; SDS: standard deviation score; SE: standard error; SEP: socioeconomic position; SES: socioeconomic status; svg: serving(s); TAG: triacylglycerol; TEI: total energy intake; wk: week(s); x: time(s); y: year(s)

Table 34 Risk of bias for randomized controlled trials examining number of eating occasions in adults and older adults and body composition and risk of obesity^a^

Article | Randomization | Deviations from intended interventions (per-protocol) | Missing outcome data | Outcome measurement | Selection of the reported result | Overall risk of bias
Bachman, 2012^87^ | LOW | LOW* | LOW | LOW | LOW | LOW
Forslund, 2008^89^ | LOW | HIGH | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Grangeiro, 2021^92^ | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS
Yildiran, 2019^101^ | SOME CONCERNS | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Zargaran, 2014^102^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS

a Possible ratings of low, some concerns, or high determined using the "Cochrane Risk-of-bias 2.0" (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898. doi:10.1136/bmj.l4898.31462531 ) *Effect of assignment

Table 35 Risk of bias for observational studies examining number of eating occasions in adults and older adults and body composition and risk of obesity^b^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Georgiopoulos, 2017^91^ | HIGH | HIGH | LOW | LOW | LOW | LOW | HIGH | HIGH
LaRose, 2019^32^ | VERY HIGH | SOME CONCERNS | LOW | SOME CONCERNS | HIGH | LOW | SOME CONCERNS | VERY HIGH
Larsen, 2019^80^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Makarem, 2020^96^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Malaeb, 2020^97^ | HIGH | SOME CONCERNS | LOW | HIGH | LOW | LOW | LOW | HIGH
Martinez, 2021^42^ | LOW* | SOME CONCERNS | LOW | LOW | HIGH | HIGH | HIGH | HIGH
Megson, 2017^43^ | HIGH | SOME CONCERNS | LOW | LOW | HIGH | LOW | HIGH | HIGH
van der Heijden, 2007^67^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | HIGH | SOME CONCERNS | HIGH

b Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the "Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)" tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.

Table 36 Evidence examining the relationship between number of eating occasions during pregnancy and gestational weight gain^a^

Study and Population Characteristics | Intervention, Comparator, and Outcome(s) | Results | Study Limitations
Samano, 2022^56^; PCS, Mexico; Analytic N=530; Study objective: To analyze whether there is an association between dietary and nutrient intake and eating habits and GWG among pregnant adolescents and their offspring’s birth weight; Participant characteristics at baseline: pregnant adolescents aged 11–19y; - Age: 15.8 (1.3)y; - Female: 100%; - Race and/or ethnicity: NR but likely majority Hispanic; - Socioeconomic position: 75% elementary education; 89% school dropout; Mostly low or very low SES; 70% single; 30% cohabitating; 89% homemakers; - Anthropometry: NR; - Physical activity: NR; - Smoking: NR; - Parity: All primigravida (inclusion criteria); - Diabetes: NR but likely none since chronic disease was an exclusion criteria; - Hypertensive Disorders: NR but likely none since chronic disease was an exclusion criteria; - TEI: 2022 (657) kcal/d; - Habitual diet at baseline: 20% had ≤2 meals/d; 56% skipped meals >1x/wk; Excluded from study or analysis: multigravida or multiple pregnancy; chronic disease; drug addictions; vegans or vegetarians; those who had a newborn with congenital malformations or stillbirth | Exposure:; Number of meals (≤2, 3, or ≥3 a day); Assessment methods and timing:; - Participants were asked about their number of meals and frequency of skipping meals (never, 1–3x/wk, 4–5x/wk); - At baseline ("during first visit", details NR); Outcomes and assessment methods:; - 1–2wk before delivery; - Gestational weight gain (GWG) calculated by subtracting self-reported initial pre-pregnancy weight from measured final gestational weight.. Adequacy of GWG was based on IOM recommendations and was categorized as inadequate or insufficient (<90%), adequate (90 to <125%), and excessive (≥125%). | [underlined: GWG adequacy percentage], PR (95% CI); Inadequate; >3 number of meals: REF; 3 number of meals: 1.03 (0.70, 1.52); <2 number of meals: 1.08 (0.70, 1.65); Excessive; >3 number of meals: REF; 3 number of meals: 1.08 (0.72, 1.64); <2 number of meals: 1.09 (0.70, 1.70) | Model adjustments:; - TEI: no; - Key confounders: age, socioeconomic position, anthropometry at baseline, parity, diabetes mellitus in the current pregnancy, hypertensive disorders in the current pregnancy; - Other: gynecological age, antenatal care; Limitations:; - Did not account for key confounders: race and/or ethnicity, physical activity; - Exposure assessment method not validated; - Timing of exposure measurement not described; - No information on non-completers; - Outcomes were based on self-reported pre-pregnancy weight; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; Instituto Nacional de Perinatología; CONACyT

a Abbreviations: CI: confidence interval; d: day(s); GWG: gestational weight gain; IOM: Institute of Medicine; NR: not reported; PCS: prospective cohort study; PR: prevalence ratio; REF: reference group; TEI: total energy intake; wk: week(s); y: year(s)

Table 37 Evidence examining the relationship between number of eating occasions during postpartum and postpartum weight change^a^

Study and Population Characteristics | Exposure, Comparator, and Outcome(s) | Results | Study Limitations
Huseinovic, 2021^93^; PCS, Secondary analysis of LEVA (Lifestyle for effective weight loss during lactation) RCT, Sweden; Analytic N=60; Study objective: To examine associations among change in eating frequency and change in energy intake and weight during a 12-week successful weight loss intervention in overweight and obese postpartum women.; Participant characteristics at baseline: Postpartum women with overweight and obesity undergoing a 12wk weight loss intervention; - Age: 33.2 (4.1)y; - Female: 100%; - Race and/or ethnicity: NR; - Socioeconomic position: 8% ≤high school; 20% ≤3y beyond high school; 72% >3y beyond high school; 95% married or cohabitating; 3% single; 2% couple with different residences; - Anthropometry: BMI 30.1 (2.7) kg/m^2^; - Physical activity: NR; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: Mean (SD) 5.9 (1.2) number of eating occasions per day (range 4–10); Excluded from study or analysis: Missing diet record at 12wk | Exposure: Eating frequency defined as the mean number of intake occasions per day. An intake occasion was defined as an energy intake of ≥50 kcal, including foods and/or beverages, separated in time from the preceding and following intake occasion by at least 30 min.; Assessment methods and timing:; - 4d diet record; - At 10–14wk postpartum and 12wk later (post-intervention at 22–26wk postpartum); Outcomes and assessment methods:; - At 10–14wk postpartum and 12wk later (post-intervention at 22–26wk postpartum); - Body weight measured to nearest 0.1 kg using electronic scale | [underlined: Change in postpartum weight (kg) by change in eating frequency over 12wk], β (SE); 0.9 (0.7), p=0.179 | Model adjustments:; - Key confounders: sex, age, socioeconomic position, anthropometry, physical activity, parity, human milk feeding; - Other: dietary treatment (intervention group); eating frequency (for weight analysis); Limitations:; - Did not account for key confounders: race and/or ethnicity, smoking; - Did not describe or account for missing data; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; Swedish Research Council; Swedish Council for Working Life and Social Research
Loy, 2019^95^; PCS, Growing Up in Singapore towards Healthy Outcomes (GUSTO), Singapore; Analytic N=687; Study objective: To examine the associations of maternal circadian eating pattern and diet quality in pregnancy with substantial postpartum weight retention at 18 months in an Asian cohort; Participant characteristics at baseline: pregnant for exposure and postpartum for outcome assessment; - Age: 31.3 (5.2)y; - Female: 100%; - Race and/or ethnicity: Ethnicity: 57% Chinese, 25% Malay, 18% Indian; - Socioeconomic position: Education 35% None/Primary/Secondary, 31% Post-Secondary,33% Tertiary; 33% Unemployed, 67% Employed; - Anthropometry: BMI at ≤14wk gestation: 23.6 (4.5) kg/m^2^; - Physical activity: 33% with <600 MET-min/wk, 50% with 600-<3000 MET-min/wk, 18% ≥3000 MET-min/wk; - Smoking: NR; - Parity: 64% with ≥1, 36% with 0; - Human Milk Feeding: 9% breastfeeding, 66% mixed feeding, 25% formula; - TEI: 1886 (654) kcal/d; - Habitual diet at baseline: Eating episodes: 31% with 1–3x/d, 32% with 4x/d, 21% with 5x/d, 16% with 6–10x/d; Excluded from study or analysis: pregnant women >15wk gestation at recruitment; aged <18y; those who became pregnant again before 18mo postpartum; missing 24h diet recall data; implausible total energy intake (<500 or >3500 kcal/d); missing data on early pregnancy weight; missing data at 18mo follow-up | Exposure: Number of eating occasions per day (≤3, 4, 5, ≥6x/d); Eating episodes were defined as events that provided ≥210 kJ (~50 kcal), with time intervals between eating episodes of ≥15min.; Assessment methods and timing:; - A 24hr recall was used to record times when meals were consumed. Eating episodes (between 1 and 10) were categorized into four groups based on its distribution: ≤3, 4, 5, and ≥6.; - At baseline (26–28wk gestation); Outcomes and assessment methods:; - At 18mo follow-up; - Postpartum weight retention (PPWR) was calculated by subtracting measured weight at first antenatal visit (≤14wk gestation) and measured weight at 18mo postpartum. Women were categorized into non-substantial PPWR (<5 kg) and substantial PPWR (≥5 kg). | [underlined: Substantial PPWR (≥5kg) at 18mo (n=687)], OR (95% CI); ≤3x/d: REF; 4x/d: 1.21 (0.64, 2.27); 5x/d: 1.97 (0.61, 2.71); ≥6x/d: 2.20 (0.94, 5.17); Complete case analysis (n=653); ≤3x/d: REF; 4x/d: 1.04 (0.55, 1.97); 5x/d: 1.13 (0.53, 2.41); ≥6x/d: 1.71 (0.72, 4.04) | Model adjustments:; - TEI: yes; - Key confounders: age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, physical activity, parity, human milk feeding; - Other: night shift; total Edinburgh Postnatal Depression Scale score; bedtime; gestational diabetes; Limitations:; - Did not account for key confounders: smoking; - Exposure data only assessed at baseline leading to a concern that changes in exposure status occurred over 18mo f/u; - High attrition rate; - Water was not accounted for in exposure assessment; Funding:; Singapore National Research Foundation; Singapore Institute for Clinical Sciences

a Abbreviations: BMI: body mass index; CI: confidence interval; d: day(s); GWG: gestational weight gain; IOM: Institute of Medicine; kcal: kilocalorie(s); kg: kilogram(s); kJ: kilojoule(s)’ mo: month(s); NR: not reported; PCS: prospective cohort study; PPWR: postpartum weight retention; REF: reference group; SD: standard deviation; SE: standard error; TEI: total energy intake; wk: week(s); y: year(s)

Table 38 Risk of bias for observational studies examining number of eating occasions in individuals during pregnancy and gestational weight gain^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Samano, 2022^56^ | HIGH | HIGH | SOME CONCERNS | LOW | HIGH | HIGH | SOME CONCERNS | VERY HIGH

a Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the "Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)" tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. )

Table 39 Risk of bias for observational studies examining number of eating occasions in individuals during postpartum and postpartum weight change^b^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Huseinovic, 2021^93^ | HIGH | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Loy, 2019^95^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | LOW | SOME CONCERNS

b Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the "Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)" tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. )

Table 40 Evidence examining the relationship between meal frequency in children and adolescents and growth, body composition, and risk of obesity^a^

Study and Population Characteristics | Intervention, Comparator, and Outcome(s) | Results | Study Limitations
Choi, 2022^78^; PCS, Korean National Health Insurance Service (NHIS), South Korea; Analytic N=26,047; Study objective: To identify the risk factors of obesity in 5yo children; Participant characteristics at baseline: children; - Age: 3y; - Female: 49%; - Race and/or ethnicity: NR but likely majority Asian; - Socioeconomic position: Mother's income level: 49% High, 32% Middle, 19% Low; - Anthropometry: NR; - Physical activity: 74% engaged in "sweat-inducing" physical activities ≥1 hr/d; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: 89% eat 3 meals/day; 69% eat 2 snacks/day and 24% eat ≥3 snacks/day; Excluded from study or analysis: no confirmed BMI, availability of an identical mother-child health insurance number, or availability of mother's BMI and income levels; mother's delivery and child's birth were not in the same year; missing availability of children's fourth (at 3y) health check-up records and birth data | Exposure: Number of meals per day (1, 2, 3, ≥4); Assessment methods and timing:; - Nutrition questionnaire at health screening on number of meals and snacks per day; - At baseline (age 3y); Outcomes and assessment methods:; - At baseline (age 3y), and 2y follow-up; - Weight and height were measured by trained personnel and used to calculate BMI. Obesity was defined as BMI ≥ sex- and age-specific 95th% according to 2007 Korean National Growth Charts. | [underlined: Obesity at 5y based on number of meals at 3y], OR (95% CI); 1x/d: 0.95 (0.25, 3.67), p=0.945; 2x/d: 1.00 (0.80, 1.25), p=0.983; 3x/d: REF; ≥4x/d: 0.80 (0.49, 1.32), p=0.384 | Model adjustments:; - TEI: no; - Key confounders: sex, age, socioeconomic position, physical activity; - Other: birth weight; developmental screening; mother's BMI; infant feeding mode; various measures of dietary behavior and intake; TV; Limitations:; - Did not account for key confounders: race and/or ethnicity, anthropometry at baseline; - Exposure data only assessed at baseline leading to a concern that changes in exposure status occurred over 2y f/u; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; No external funding
Elgar, 2005^15^; PCS, Health Behaviour of School-aged Children Study, UK; Analytic N=355; Study objective: To study the prevalence and stability of overweight and obesity in a cohort of adolescents, and the effects of sedentary behavior and physical activity on changes in body mass.; Participant characteristics at baseline: adolescents 11–14y; - Age: 12.3 (6.3)y; - Female: 55%; - Race and/or ethnicity: NR; - Socioeconomic position: NR; - Anthropometry: 20% with overweight/obesity; - Physical activity: NR; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: NR; Excluded from study or analysis: missing data at baseline or follow-up; in private or special needs schools; incarcerated | Exposure:; Lunch (number skipped per week) Dinner (number skipped per week); Assessment methods and timing:; - Questionnaire with items related to dieting and meal skipping; - At baseline; Outcomes and assessment methods:; - At baseline, 4y follow-up; - Weight and height were measured by study personnel and used to calculate BMI. | [underlined: BMI (kg/m^2^) at 4y follow up], β (SE); Lunch meals skipped per week: 0.03 (0.16), p=NS Dinner meals skipped per week: 0.12 (0.14), p=NS | Model adjustments:; - TEI: no; - Key confounders: sex, age, socioeconomic position, anthropometry at baseline, physical activity; - Other: number of other meals skipped; number of hours per week spent watching television or videos, or playing computer games; Limitations:; - Did not account for key confounders: race and/or ethnicity; - Exposure was only measured at baseline and subject to measurement error; - Did not provide evidence as to whether the result was unbiased due to missing data; - No preregistered data analysis plan; - Water was not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; Welsh Assembly Government
Field, 2010^104^; PCS, Growing Up Today Study, U.S.; Analytic N=4,456; Study objective: To assess the relation of dietary and physical activity weight-control strategies, alone and together, with subsequent weight change; Participant characteristics at baseline: female adolescents and young adults (14–22y); - Age: 17.6 (1.6)y; - Female: 100%; - Race and/or ethnicity: White: >90%; - Socioeconomic position: All children of nurses; - Anthropometry: BMI 22.1 (3.4) kg/m^2^; - Physical activity: 48% exercise to control weight; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: 20% skip meals; Excluded from study or analysis: males; missing data on weight control behaviors; weight change outliers | Exposure: Meal skipping (yes/no); Assessment methods and timing:; - Detailed assessment of dieting adapted from YRBS, including meal skipping; - At baseline (2001); Outcomes and assessment methods:; - At baseline (2001), and 4y follow-up (2005); - Weight and height were self-reported and used to calculate BMI. Overweight and obesity were defined based on age-and-sex specific IOTF classifications. | [underlined: Change in weight (kg) over 4y by skipping meals], Mean (95% CI); −0.0 (−0.5, 0.5) | Model adjustments:; - TEI: no; - Key confounders: sex, age, anthropometry at baseline; - Other: television time; Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position, physical activity; - Exposure was not well defined, was subject to measurement error, and only assessed at baseline; - No evidence whether the result was biased due to missing data; - Outcome was self-reported; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; NIH
Franko, 2008^105^; PCS, NHLBI Growth and Health Study, U.S.; Analytic N=2,375; Study objective: To document meal frequency and its relationship to body mass index; Participant characteristics at baseline: Black and White adolescent females; - Age: 9–10y; - Female: 100%; - Race and/or ethnicity: White: 49%; Black: 51%; - Socioeconomic position: NR; - Anthropometry: NR; - Physical activity: NR; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: 15% consumed ≥3 meals on all 3 days of food record; Excluded from study or analysis: lost to follow-up | Exposure: Meal frequency (# of days out of 3 days of eating ≥3 meals); Assessment methods and timing:; - 3-day food records; dietitians rated each eating event as a "meal" or "snack" and the number of days (out of 3 possible) that a girl consumed ≥3 meals was computed for each girl at each visit; - At baseline, and 3–5, 7, 8, and 10y follow-up; Outcomes and assessment methods:; - At baseline, and 2–10y follow-up (annually); - Height and weight were measured by study personnel and used to calculate BMI-for-age z scores based on CDC reference values. Overweight was defined as age- and gender-specific BMI ≥95th percentile. | [underlined: BMIz by each additional day of consuming ≥3]; [underlined: meals over 3–10y visits], β (SE); −0.0472 (0.0077), p<0.0001; [underlined: Overweight by each additional day of consuming]; [underlined: ≥3 meals over 3–10y visits], OR (95% CI); All girls: 0.91 (0.79, 1.05), p=NS; Black girls: 0.81 (0.67, 0.95); White girls: 0.98 (0.85, 1.19) | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, physical activity; - Other: study year; study site; hours watching TV per week; Limitations:; - Exposure was not well defined and was subject to measurement error; - Did not provide evidence as to whether the result was unbiased due to missing data; - No preregistered data analysis plan; - Water was not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; NHLBI
Lee, 2012^81^; PCS, Obesity and Metabolic Disorders Cohort in Childhood, South Korea; Analytic N=1504 (474 first graders, 1030 fourth graders); Study objective: To assess risk factors associated with children's body mass index and their changes over a 2-year period; Participant characteristics at baseline: Korean 1st and 4th grade children; - Age: 7.3(0.3)y and 10.0(0.4)y; - Female: 51%; - Race and/or ethnicity: NR but majority likely Asian; - Socioeconomic position: 33% ≤12y maternal education; 23% ≤12y paternal education; 70% >3 million Korean Wan; 89% with two parent household; - Anthropometry: BMI 16.0 (2.3) kg/m^2^ in first graders, 18.1 (3.0) kg/m^2^ in fourth graders; - Physical activity: Exercise ≥5 days/wk: 17% first graders, 13% fourth graders; - Smoking: NR; - TEI: 1800 (300) kcal/d in first graders, 1700 (400) in fourth graders; - Habitual diet at baseline: 28% meal skipping during a week; Excluded from study or analysis: missing data | Exposure: Meal skipping during the week (yes/no); Assessment methods and timing:; - Three 24hr recalls (two weekdays and one weekend) was used to collect data on frequency of skipping meals and snack intake; - At baseline; Outcomes and assessment methods:; - At baseline, 2y follow-up; - Height and weight were measured by trained personnel and used to calculate BMI. BMI percentile was based on age and sex specific 2007 growth chart for Korean children. | [underlined: Change in BMI (kg/m^2^) during 2y follow-up], β (95% CI); 1st graders; No meal skipping: REF; Meal skipping: 0.021 (−0.013, 0.055) p=0.232; 4th graders; No meal skipping: REF; Meal skipping: 0.002 (−0.029, 0.033) p=0.884 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, socioeconomic position, anthropometry at baseline, physical activity; - Other: screen time; sleep duration; parental BMI; sexual maturation; Limitations:; - Did not account for key confounders: race and/or ethnicity; - Exposure data only assessed at baseline leading to a concern that changes in exposure status occurred over 2y f/u; - No information on non-completers; - No preregistered data analysis plan; - Unclear if water/beverages were accounted for in exposure assessment; Funding:; NR
Narla, 2019^45^; PCS, NHLBI Growth and Health Study, U.S.; Analytic N=2,024; Study objective: To rank the importance of potentially modifiable psychosocial, dietary, behavioral and environmental risk and protective factors for female adolescent obesity; Participant characteristics at baseline: Black and White adolescent females; - Age: 10y; - Female: 100%; - Race and/or ethnicity: White: 48%; Black: 52%; - Socioeconomic position: Parental education: 24%<high school, 36% college graduate; 40% post-graduate; Household income 16%≤$9,999; 13.5% $10k–19,999; 29% $20k-39,999; 36% ≥$40k; 5.5% not available; - Anthropometry: BMI 18.5 kg/m^2^; - Physical activity: NR; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: NR; Excluded from study or analysis: missing outcome data | Exposure: Skip lunch (yes/no); Assessment methods and timing:; - 3d food diary (included 1 weekend day); - At baseline (age 9–10y); Outcomes and assessment methods:; - At baseline, and 10y follow-up (age 19y); - Body fat percentage was measured by sum of skinfolds measured by study personnel | [underlined: Body fat % at 10y follow-up by skipping lunch at baseline], β (SE); 6.58 (1.49), p=0.00 | Model adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline; - Other: parent education; Limitations:; - Did not account for key confounders: physical activity; - Exposure data only assessed at baseline leading to a concern that changes in exposure status occurred over f/u; - Exposure were not well defined and subject to measurement error; - No preregistered data analysis plan; - Water/beverages were not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; Stanford Medical Scholars Program; NIA
Neumark-Sztainer, 2007^46^; PCS, Project EAT, U.S.; Analytic N=2,380; Study objective: To examine the prevalence of adolescent overweight, binge eating, and use of extreme weight-control behaviors, and their simultaneous occurrence.; Participant characteristics at baseline: ethnically and socioeconomically diverse adolescents; - Age: 12.8 (0.8)y −15.8 (0.8)y; - Female: 55%; - Race and/or ethnicity: White: 49%; African American: 19%; Asian: 19%; Native American: 3%, Mixed or other: 4%; Hispanic: 6%; - Socioeconomic position: NR; 37% of low or low-middle SES; - Anthropometry: ~25% overweight; - Physical activity: NR; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: NR; Excluded from study or analysis: missing data | Exposure: Lunch (days/wk); Dinner (days/wk); Assessment methods and timing:; - “During the past week, how many days did you eat breakfast/lunch/dinner?”; - At baseline; Outcomes and assessment methods:; - At baseline, 5y follow-up; - Height and weight were self-reported and BMI was calculated. Adolescents with BMI values above the 85th percentile for gender and age were classified as overweight. | [underlined: Overweight at 5y follow-up based on baseline meal frequency], OR; Lunch; Girls: 0.99, p=0.682; Boys: 0.93, p=0.121; Dinner; Girls: 0.95, p=0.247; Boys: 0.90, p=0.100 | Model adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline; - Other:; Limitations:; - Did not account for key confounders: physical activity; - Exposure data only assessed at baseline leading to a concern that changes in exposure status occurred over f/u; - No information on non-completers; - Outcomes were self-reported; - No preregistered data analysis plan; - Water was not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; Maternal and Child Health Bureau
Neumark-Sztainer, 2012^106^; PCS, Project EAT, U.S.; Analytic N=1,902; Study objective: To examine 10-year longitudinal associations between dieting and unhealthy weight control behaviors and changes in body mass index from adolescence to young adulthood.; Participant characteristics at baseline: middle and high school students; - Age: 13 (0.7)y −16 (0.8)y; - Female: 49%; - Race and/or ethnicity: White: 50%; African American: 18%; Asian: 19%; Native American: 3%, Mixed or other: 5%; Hispanic: 5%; - Socioeconomic position: NR; - Anthropometry: NR; - Physical activity: NR; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: 27% reported skipping meals at baseline; Excluded from study or analysis: missing data at one of the time points; pregnant | Exposure: Skipping meals (yes/no); Assessment methods and timing:; - “Have you done any of the following things in order to lose weight or keep from gaining weight during the past year?” Behaviors included skip meals.; - At baseline; Outcomes and assessment methods:; - At baseline, 10y follow-up; - Weight and height were self-reported and used to calculate BMI | [underlined: Change in BMI (kg/m^2^) over 10y by baseline meal skipping], Mean (SE); Females; No skipping meals: 3.12 (0.22); Skipping meals: 4.14 (0.24) p=0.002; Males; No skipping meals: 3.85 (0.15); Skipping meals: 4.83 (0.33) p=0.007 | Model adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline; - Other: cohort; Limitations:; - Did not account for key confounders: physical activity; - Exposure data only assessed at baseline leading to a concern that changes in exposure status occurred over 1y f/u; - Exposure not well defined and subject to measurement error; - No evidence whether the result was biased due to missing data; - Outcomes were self-reported; - No preregistered data analysis plan; - Water was not accounted for in exposure assessment; Did not adjust for TEI; Funding:; NR
Quick, 2013^54^; PCS, Project EAT, U.S.; Analytic N=2,134; Study objective: To identify 10-year longitudinal predictors of overweight incidence during the transition from adolescence to young adulthood; Participant characteristics at baseline: diverse adolescent population; - Age: 15 (1.6)y; - Female: 53%; - Race and/or ethnicity: White: 49%; Black: 18%; Asian: 18%; Native American: 3%; Other: 5%; Hispanic: 6%; - Socioeconomic position: NR; Low income: 16%; - Anthropometry: 25% overweight; - Physical activity: ~6.8 (4.5) hr/wk MVPA; - Smoking: NR; - TEI: ~2000 (1000) kcal/d; - Habitual diet at baseline: lunch ~5.5 times/wk, dinner ~6 times/wk; Excluded from study or analysis: missing data at baseline or follow-up; not overweight at baseline | Exposure: Lunch (days/wk); Dinner (days/wk); Assessment methods and timing:; - “During the past week, how many days did you eat breakfast/lunch/dinner?”; - At baseline, 10y follow-up; Outcomes and assessment methods:; - At baseline, 10y follow-up; - Self-reported height and weight were used to calculate BMI. Weight status at Time 3 was defined according to current BMI guidelines for adults (overweight: BMI ≥25 kg/m^2^) | [underlined: Overweight at 10y follow-up], OR (95% CI); Based on baseline lunch frequency; Females: 0.94 (0.87, 1.01); Males: 0.99 (0.91, 1.07); Based on 10y change in lunch frequency; Females: 1.00 (0.92, 1.09); Males: 1.13 (1.03, 1.23), p<0.05; Based on baseline dinner frequency; Females: 0.88 (0.81, 0.95), p<0.05; Males: 1.02 (0.90, 1.16); Based on 10y change in dinner frequency; Females: 0.94 (0.84, 1.05); Males: 1.14 (1.00, 1.29), p<0.05 | Model adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline; - Other: time 1 predictor variable; Limitations:; - Did not account for key confounders: physical activity; - Did not provide evidence as to whether the result was unbiased due to missing data; - Outcomes were self-reported; - No preregistered data analysis plan; - Water was not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; NHLBI
Ritchie, 2012^84^; PCS, NHLBI Growth and Health Study, U.S.; Analytic N=2,146; Study objective: To assess the prospective relation of an objective measure of eating frequency with adiposity in girls from ages 9–10 to 19–20y.; Participant characteristics at baseline: Black and White adolescent females; - Age: 9–10y; - Female: 100%; - Race and/or ethnicity: White: 49%; Black: 51%; - Socioeconomic position: 8.59 (3.43) maximum years of parental education by either parent; - Anthropometry: BMI 18.6 (3.8) kg/m^2^; - Physical activity: "sometimes" physically active; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: Meals 2.6 (0.5) times/d; Excluded from study or analysis: not age within 2wk of 9–10y, black or white, living with parents or guardians with racial concordance, and parent or guardian providing information on the demographic characteristics; not missing data on any control variables | Exposure: Meal frequency (1–2.5 times/d vs >2.5 times/d); Assessment methods and timing:; - 3d diet record; - At baseline (averaged over 2 visits at ages 9–11y); Outcomes and assessment methods:; - At baseline, 10y follow-up; - Height, weight, and waist circumference (WC) were measured by trained examiners. BMI was calculated from height and weight. | [underlined: Change in WC (cm) over 10y based on baseline meal frequency], Mean (SE); ALL; 1–2.5x/d: 11.34 (0.60); >2.5x/d: 11.75 (0.58) p=NS; BLACK; Lower meal frequency associated with greater increases in WC, p=0.052; WHITE; Data NR; [underlined: Change in BMI (kg/m^2^) over 10y based on baseline meal frequency], Mean (SE); 1–2.5x/d: 7.00 (0.23); >2.5x/d: 7.43 (0.22) p=0.035; BLACK; Lower meal frequency associated with greater increases in BMI, p=0.004; WHITE; Data NR | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, physical activity; - Other: dieting for weight loss, TV/video viewing; Limitations:; - Exposure data only assessed at baseline leading to a concern that changes in exposure status occurred over 10y f/u; - No information on non-completers; - No preregistered data analysis plan; - Beverages was not accounted for in exposure assessment; Funding:; USDA; NIH
Stea, 2015^107^; PCS, Norway; Analytic N=428; Study objective: To investigate meal pattern longitudinally and explore whether meal skipping was associated with overweight among Norwegian children and adolescents; Participant characteristics at baseline:; Norwegian 4th grade children; - Age: 9–10y; - Female: 52%; - Race and/or ethnicity: NR; - Socioeconomic position: 56% parents with university/college education; - Anthropometry: 3% underweight, 81% normal weight, 14% overweight, 2% obesity; - Physical activity: ~3.3 hr/wk of physical activity outside school; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: 47% regular all 4 meals; 67% regular evening meal; 85% regular dinner; 81% regular lunch; 91% regular breakfast; Excluded from study or analysis: missing data | Exposure: Meal skipping (4 categories based on behavior at 4th and 7th grade); - Continued skippers: skipping meals at both time points; - Start all meals: meal skipping in 4th grade, eat all meals at 7th grade; - Stop all meals: eat all meals in 4th grade, meal skipping in 7th grade; - All meals: eat all meals at both time points (no meal skipping at both time points); Assessment methods and timing:; - Parents completed a retrospective FFQ on their child's intake during the last 6mo. Children who ate main meals <7 d/wk were classified as breakfast, lunch, dinner, and evening-meal skippers. Children who ate main meals every day were classified as regular breakfast, lunch, dinner and evening meal consumers. These dichotomous variables were then combined to create a summary variables for those eating all meals vs those skipping meals in 4th and 7th grade.; - At baseline (4th grade), and 3y follow-up (7th grade); Outcomes and assessment methods:; - At baseline (4th grade), and 3y follow-up (7th grade); - Height and weight were measured by nurses and used to calculate BMI. Overweight/obesity was based on IOTF sex- and age-specific cut-off points. | [underlined: Overweight/obesity in 7th grade], OR (95% CI) Eats all meals (No skipping): REF; Continued skipping: 1.8 (0.5, 6.2); Start all meals: 1.4 (0.3, 7.2); Stop all meals: 2.8 (0.7, 11.9); . | Model adjustments:; - TEI: no; - Key confounders: sex, age, socioeconomic position, anthropometry at baseline, physical activity; - Other: meal pattern; Limitations:; - Did not account for key confounders: race and/or ethnicity; - High attrition rate/missing data; - No preregistered data analysis plan; - Unclear if water/beverages were accounted for in exposure assessment; - Did not adjust for TEI; Funding:; Telemark University College; Telemark Hospital; Research Council of Norway; Public Health Programme of Telemark
Viner, 2006^69^; PCS, 1970 British Birth Cohort, UK; Analytic N=5,154; Study objective: To examine whether factors common to obesity prevention programmes in adolescence, namely exercise, sedentary activities, eating behaviours and psychological factors, predict change in BMI in 'free-living' adolescents followed into adulthood; Participant characteristics at baseline: adolescents; - Age: 16y; - Female: 51%; - Race and/or ethnicity: NR; - Socioeconomic position: NR; - Anthropometry: 8% with obesity; - Physical activity: 42% higher than average participation in sports; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: 80% ate evening meal with parents daily; Excluded from study or analysis: missing data | Exposure: Weekly frequency of eating evening meal with parents (never, 1–3x/wk, daily); Assessment methods and timing:; - Children reported the number of times per week they ate evening meals with their parents; - At baseline (age 16y); Outcomes and assessment methods:; - At baseline (age 16y), and 14y follow-up (age 30y); - Weight and height were measured at 16y and self-reported at 30y. BMI z-scores (BMIz) at 16y was calculated using UK 1990 growth reference; at 30y, BMIz was calculated separately for each sex from the cohort mean and standard deviation. | [underlined: Change in BMIz from 16y to 30y], β (95% CI); Based on weekly frequency of eating weekday evening meals with parents; Never: REF; 1–3x/wk: −0.09 (−0.22, 0.04), p=0.2; Daily: −0.06 (−0.17, 0.05), p=0.3 | Model adjustments:; - TEI: no; - Key confounders: sex, age, socioeconomic position, anthropometry at baseline; - Other: none; Limitations:; - Did not account for key confounders: race and/or ethnicity, physical activity; - Exposure assessment method not validated and exposure data only assessed at baseline leading to a concern that changes in exposure status occurred over f/u; - No information on non-completers; - Outcomes were self-reported; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; NR
Wijtzes, 2016^71^; PCS, Generation R, The Netherlands; Analytic N=5,913; Study objective: To assess the prospective associations of breakfast, lunch, and dinner skipping at age 4 years with body fat (i.e., percent fat mass, body mass index, and weight status) at age 6 years.; Participant characteristics at baseline: birth cohort; - Age: 4y; - Female: 50%; - Race and/or ethnicity: Dutch ethnic background: 56%; ; Other Western: 9%; Non-Western: 35%; - Socioeconomic position: 46% with mother of low or mid-low education; 52% low or middle household income; 75% with employed mother; - Anthropometry: 82% normal weight; 18% overweight; - Physical activity: NR; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: 7% skipped lunch, and 7% skipped dinner; Excluded from study or analysis: missing data on BMI and fat mass, 2nd or 3rd children of the same mother | Exposure: Lunch skipping (yes/no; categorical); Dinner skipping (yes/no; categorical); Categories of meal skipping based on consumption at age 4y and 6y:; - Stable meal consumption (i.e., meal consumption at both ages); - table meal skipping (i.e., meal skipping at both ages); - Decrease in meal skipping (i.e., meal skipping at 4y and meal consumption at 6y); - Increase in meal skipping (i.e., meal consumption at 4y and meal skipping at 6y); Assessment methods and timing:; - Children’s weekly consumption of lunch and dinner was assessed by parent questionnaire at baseline (“never,” “1–2 days per week,” “3–4 days per week,” “5–6 days per week,” and “every day” (coded as 0–5) and at 2y f/u ( weekdays (coded as 0–5) and weekend days (coded as 0–2), and the scores were summed to calculate total weekly consumption (0–7). Because of highly skewed distributions, meal skipping was defined as consumption <7 days/wk.; - At baseline, 2y follow-up; Outcomes and assessment methods:; - At baseline, 2y follow-up; - Height and weight were measured by study personnel and used to calculate BMI. BMI SDS adjusted for age and sex were constructed based on Dutch reference growth curves. Overweight/obesity was defined according to IOTF age- and sex-specific cutoff points. Fat mass was measured using DEXA | [underlined: BMI SDS at 6y], β (95% CI); Based on lunch at 4y; Lunch consumption: REF; Lunch skipping: −0.06 (−0.15, 0.04); Based on lunch at 4y and 6y; Stable lunch consumption: REF; Stable lunch skipping: −0.09 (−0.22, 0.04); Decrease in lunch skipping: −0.09 (−0.21, 0.04); Increase in lunch skipping: 0.01 (−0.06, 0.08); Based on dinner at 4y; Dinner consumption: REF; Dinner skipping: −0.01 (−0.09, 0.07); Based on dinner at 4y and 6y; Stable dinner consumption: REF; Stable dinner skipping: 0.09 (−0.14, 0.33); Decrease in dinner skipping: −0.00 (−0.10, 0.10); Increase in dinner skipping: 0.04 (−0.16, 0.25); [underlined: % Fat Mass at 6y], β (95% CI); Based on lunch at 4y; Lunch consumption: REF; Lunch skipping: −0.31 (−0.99, 0.36); Based on lunch at 4y and 6y; Stable lunch consumption: REF; Stable lunch skipping: −0.33 ( −1.24, 0.58); Decrease in lunch skipping: −0.59 ( −1.26, 0.08); Increase in lunch skipping: 0.01 (−0.49, 0.51); Based on dinner at 4y; Dinner consumption: REF; Dinner skipping: 0.04 (−0.69 to 0.77); Based on dinner at 4y and 6y; Stable dinner consumption: REF; Stable dinner skipping: 0.17 ( −1.45, 1.79); Decrease in dinner skipping: −0.10 (−0.68, 0.48); Increase in dinner skipping: 0.65 (−0.39, 1.68); [underlined: Overweight/Obesity at 6y], OR (95% CI); Based on lunch at 4y; Lunch consumption: REF; Lunch skipping: 1.05 (0.67, 1.66); Based on lunch at 4y and 6y; Stable lunch consumption: REF; Stable lunch skipping: 0.88 (0.34, 2.27); Decrease in lunch skipping: 1.14 (0.54, 2.39); Increase in lunch skipping: 1.07 (0.65, 1.76); Based on dinner at 4y; Dinner consumption: REF; Dinner skipping: 0.87 (0.48, 1.60); Based on dinner at 4y and 6y; Stable dinner consumption: REF; Stable dinner skipping: 0.34 (0.05, 2.20); Decrease in dinner skipping: 0.81 (0.43, 1.52); Increase in dinner skipping: 0.95 (0.29, 3.09) | Model adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, physical activity; - Other: other meal skipping behaviors; parental BMI; children's lifestyle behaviors; Limitations:; - Exposure data only assessed at baseline leading to a concern that changes in exposure status occurred over f/u; - No preregistered data analysis plan; - Water was not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; Erasmus Medical Center Rotterdam; Erasmus University Rotterdam; Netherlands Organization for Health Research and Development

a Abbreviations: ALT: alanine aminotransferase; AST: aspartate aminotransferase; AUD: Australian Dollar; β: beta coefficient; BMI: body mass index; BMIz: body mass index z-score; BP: blood pressure; CDC: Centers for Disease Control and Prevention; CI: confidence interval; cm: centimeter(s); d: day(s); DEXA: dual energy x-ray absorptiometry; FFQ: food frequency questionnaire; g: gram(s); GGT: gamma-glutamyl transferase; HbA1c: hemoglobin A1C; HOMA-IR: Homeostatic Model Assessment of Insulin Resistance; hr: hour(s); HR: hazard ratio; IOTF: International Obesity Task Force; IQR: interquartile range; kcal: kilocalorie(s); kg: kilogram(s); lb: pound(s); m: meter(s); MET: metabolic equivalent; min: minute(s); mm: millimeter(s); MVPA: moderate to vigorous physical activity; N/A: not applicable; NCC: nested case control study; NCI: National Cancer Institute; NHLBI: National Heart, Lung, and Blood Institute; NICHD; Eunice Kennedy Shriver National Institute of Child Health and Human Development; NIDDK: National Institute of Diabetes and Digestive and Kidney Diseases; NIH: National Institutes of Health; NISOC: nmol: nanomole; NR: not reported; NS: not significant; OR: odds ratio; PCS: prospective cohort study; Project EAT: Project Eating and Activity over Time; RCS: retrospective cohort study; REF: reference group; RMB: renminbi (Chinese yuan); RR: risk ratio; SD: standard deviation; SDS: standard deviation score; SE: standard error; SEP: socioeconomic position; SES: socioeconomic status; svg: serving(s); TAG: triacylglycerol; TEI: total energy intake; wk: week(s); x: time(s); y: year(s)

Table 41 Risk of bias for observational studies examining meal frequency in children and adolescents and growth, body composition, and risk of obesity^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Choi, 2022^78^ | HIGH | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Elgar, 2005^15^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Field, 2010^104^ | HIGH | HIGH | LOW | LOW | HIGH | HIGH | SOME CONCERNS | VERY HIGH
Franko, 2008^105^ | LOW* | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Lee, 2012^81^ | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Narla, 2019^45^ | SOME CONCERNS | HIGH | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Neumark-Sztainer, 2007^46^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | HIGH | SOME CONCERNS | HIGH
Neumark-Sztainer, 2012^106^ | SOME CONCERNS | HIGH | LOW | LOW | HIGH | HIGH | SOME CONCERNS | HIGH
Quick, 2013^54^ | SOME CONCERNS | LOW | LOW | LOW | HIGH | HIGH | SOME CONCERNS | HIGH
Ritchie, 2012^84^ | LOW* | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Stea, 2015^107^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Viner, 2006^69^ | HIGH | VERY HIGH | LOW | LOW | HIGH | HIGH | HIGH | VERY HIGH
Wijtzes, 2016^71^ | LOW* | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS

a Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the "Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)" tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.

Table 42 Evidence examining the relationship between meal frequency in adults and older adults and body composition and risk of obesity^a^

Study and Population Characteristics | Intervention, Comparator, and Outcome(s) | Results | Study Limitations
Chu, 2021^103^; PCS, National Longitudinal Study of Adolescent to Adult Health (Add Health), U.S.; Analytic N=12,155; Study objective: To determine the association in a large national sample of young adults between weight goals, weight control behaviors, and BMI at 7- and 15-year follow-up; Participant characteristics at baseline: young adults aged 18–26y; - Age: 22 (0.12)y; - Female: 54%; - Race and/or ethnicity: Non-Hispanic White: 68%; Non-Hispanic Black/African American: 16%; Non-Hispanic Asian/Pacific Islander: 3%; American Indian/Native American: 1%; Other: 1%; Hispanic/Latino: 12%; - Socioeconomic position: Household income ~$45,990; - Anthropometry: BMI 26.5 (0.13) kg/m^2^; - Physical activity: 36% exercise for weight loss/maintenance; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: 9% fasting/skipping meals; Excluded from study or analysis: loss of follow-up or missing data on outcomes or covariates | Exposure: Fasting/skipping meals in order to lose/maintain weight (yes/no); Assessment methods and timing:; - Those who reported a weight loss/maintenance goal were asked to describe whether or not you engaged in specific behaviors to lose/maintain weight during the past 7 days, including fasting/skipping meals; - At baseline; Outcomes and assessment methods:; - At baseline, 7y follow-up, 15y follow-up; - Weight and height were either measured (85% at 7y f/u, 43% at 15y f/u) or self-reported and used to calculate BMI | [underlined: Change in BMI (kg/m^2^) "at 7- and 15-y follow-up"], β (95% CI); Men; BMI <18.5: 5.91 (2.96, 8.86), p<0.001; BMI 18.5–25: 0.18 (−0.27, 0.64), p=0.419; BMI >25: 0.15 (−0.17, 0.47), p=0.37; Women; BMI <18.5: 0.03 ( −1.27, 1.33), p=0.960; BMI 18.5–25: 0.38 (0.13, 0.64), p=0.003; BMI >25: 0.25 (−0.04, 0.53), p=0.088 | Model adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline; - Other: wave; Limitations:; - Did not account for key confounders: physical activity, smoking; - Exposure data only assessed at baseline leading to a concern that changes in exposure status occurred over 1y f/u; - Exposure not well defined and subject to measurement error; - No evidence whether the result was biased due to missing data; - Outcomes were self-reported; - No preregistered data analysis plan; - Water was not accounted for in exposure assessment; Did not adjust for TEI; Funding:; NICHD
Larsen, 2019^80^; PCS, Danish Monitoring Trends and Determinants in Cardiovascular Disease (MONICA) study, Denmark; Analytic N=2,124; Study objective: To examine the associations between eating frequency and 6-y changes in BMI, fat mass, fat-free mass, body fat percentage, and waist circumference.; Participant characteristics at baseline: middle-aged adults; - Age: 46 (36–66)y; - Female: 49%; - Race and/or ethnicity: NR; Socioeconomic position: 30% ≤ primary level education; - Anthropometry: BMI 24 (20–32) kg/m^2^; - Physical activity: 23% inactive/sedentary; - Smoking: 50% never; - TEI: NR; - Habitual diet at baseline: Eats 4 (2, 6) times/d; 3 (2, 4) meals per day and 1 (0, 3) snacks per day; Excluded from study or analysis: missing data on eating frequency, adiposity measures, or covariates; prevalent cancer, cardiovascular disease, self-reported diabetes prior to health exam | Exposure: Meal frequency (times/d); Assessment methods and timing:; - Participants completed a survey and reported how many meals they ate during the day and how often they snacked between meals.; - At T1 (1982–1983), and T2 (1987–1988); Outcomes and assessment methods:; - At T1 (1982–1983), T2 (1987–1988), and T3 (1993–1994); - Height, weight, and waist circumference (WC) were measured. Body fat percentage (BF%) was measured using bioelectric impedance. BMI, fat-mass index (FMI), and fat-free mass index (FFMI) were calculated. | [underlined: 6y change in FMI (kg/m^2^) from T2-T3], β (95% CI); Based on meal frequency at T2; −0.10 (−0.20, −0.00), p=0.04; Based on 5yΔ in meal frequency from T1-T2; −0.10 (−0.21, 0.01), p=0.06; [underlined: 6y change in FFMI (kg/m^2^) from T2-T3], β (95% CI); Based on meal frequency at T2; −0.04 (−0.08, 0.00), p=0.07; Based on 5yΔ in total eating frequency from T1-T2; −0.05 (−0.09, −0.00), p=0.05; [underlined: 6y change in BF% from T2-T3], β (95% CI); Based on meal frequency at T2; −0.17 (−0.40, 0.06), p=0.15; Based on 5yΔ in meal frequency from T1-T2; −0.16 (−0.41, 0.08), p=0.20; [underlined: 6y change in WC (cm) from T2-T3], β (95% CI); Based on meal frequency at T2; −0.49 (−0.99, 0.00), p=0.05; Based on 5yΔ in meal frequency from T1-T2; −0.41 (−0.95, 0.12), p=0.13; Among subsample (n=314) with TEI:; p=NS for FMI, FFMI, BF%, and WC; p=NS for effect modification by gender or obesity status; [underlined: 6y change in BMI (kg/m^2^) from T2-T3], β (95% CI); Based on meal frequency at T2; −0.14 (−0.27, −0.00), p=0.04; Based on 5yΔ in meal frequency from T1-T2; −0.14 (−0.28, 0.00), p=0.05; Among subsample (n=314) with TEI:; p=NS for BMI; p=NS for effect modification by gender or obesity status | Model adjustments:; - TEI: yes, in a subsample of 314 participants; - Key confounders: sex, age, socioeconomic position, anthropometry at baseline, physical activity, smoking; - Other: alcohol intake; menopausal status for women; height (for WC); baseline intake of snacks or meals; Limitations:; - Did not account for key confounders: race and/or ethnicity; - Exposure assessment method not validated; - High attrition rate/missing data; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; - Did not adjust for TEI in full sample; Funding:; No external funding
Odegaard, 2013^50^; PCS, Coronary Artery Risk Development in Young Adults (CARDIA), U.S.; Analytic N=1138 (abdominal obesity); 1064 (obesity); Study objective: To examine breakfast intake frequency with incidence of metabolic conditions; Participant characteristics at baseline: young black and white adults; - Age: ~32(3)y; - Female: 56%; - Race and/or ethnicity: White: 54%; Black: 46%; - Socioeconomic position: Education: ~14(2)y; - Anthropometry: BMI ~26(6) kg/m^2^; - Physical activity: ~330 exercise units/wk; - Smoking: 26% current; 16% former; - TEI: ~2760 (1200) kcal/d; - Habitual diet at baseline: 43% ate breakfast 0–3 days/wk, 22% 4–6 days/wk, and 35% daily; Excluded from study or analysis: did not participate in any clinical exam in years 10–25; diabetes at baseline; missing dietary data or with reported energy intakes outside 800–8,000 kcal/day for men and 600–6,000 kcal/day for women; missing data on alcohol, smoking, or physical activity); participants prevalent with the condition at year 7 | Exposure: Lunch and dinner frequency (days/wk); Assessment methods and timing:; - Interview-administered CARDIA diet history questionnaire; - Baseline (year 7), and year 20; Outcomes and assessment methods:; - Baseline (year 7), and years 10, 15, 20, and 25; - Height, weight, and waist circumference were measured by staff at each clinical examination. Obesity defined as BMI ≥30 kg/m^2^ and abdominal obesity as waist circumference >88cm for women or >102 cm for men. | [underlined: Abdominal obesity], HR (95% CI); Lunch frequency p=NS, data not shown Dinner frequency p=NS, data not shown; [underlined: Obesity], HR (95% CI) Lunch frequency p=NS, data not shown Dinner frequency p=NS, data not shown | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, physical activity, smoking; - Other: study center; alcohol consumption; fast food restaurant use; diet quality score; frequency of lunch/dinner and morning/afternoon/evening snacks; Limitations:; - Did not account for those with missing data; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; Funding:; NHLBI; NIDDK; Bell Institute of Health and Nutrition at General Mills
Phelan, 2008^52^; PCS, National Weight Control Registry, U.S.; Analytic N=257 (post-holiday); 252 (1mo f/u); Study objective: To systematically compare the behaviors of successful weight losers vs normal weight losers before, during, and after the winter holiday season; Participant characteristics at baseline: adults with successful weight loss; - Age: ~46 (12)y; - Female: 75%; - Race and/or ethnicity: Caucasian: 96%; - Socioeconomic position: 73% ≥college education; - Anthropometry: BMI 25.5 (6.4) kg/m^2^ among successful weight losers; 21.8 (1.9) kg/m^2^ among normal weight participants; - Physical activity: NR; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: NR; Excluded from study or analysis: age <18y; among successful weight losers, those that did not maintain weight loss ≥30 lbs for ≥1 yr; among normal weight participants, those with BMI <18.5 or ≥25 kg/m^2^ | Exposure: Lunch frequency (days/wk) and dinner frequency (days/wk); Assessment methods and timing:; - “Over the past month, on average how many days per week did you eat____(breakfast, lunch, dinner, snacks, and dessert/sweets); - Before the holiday (Nov), and after the holiday (Jan); Outcomes and assessment methods:; - Before the holiday (Nov), after the holiday (Jan), and at 1mo follow-up (Feb); - Weight was self-reported | [underlined: Change in weight over 2mo (pre-holiday to post-holiday) based on pre-holiday lunch frequency]; Data NR, p=NS; [underlined: Change in weight over 3mo (pre-holiday to 1mo after the holiday) based on pre-holiday lunch frequency]; Data NR, p=NS; [underlined: Change in weight over 2mo (pre-holiday to post-holiday) based on pre-holiday dinner frequency]; Data NR, p=NS; [underlined: Change in weight over 3mo (pre-holiday to 1mo after the holiday) based on pre-holiday dinner frequency]; Data NR, p=NS | Model adjustments:; - TEI: no; - Key confounders: anthropometry at baseline; - Other: none; Limitations:; - Did not account for key confounders: sex, age, race and/or ethnicity, socioeconomic position, physical activity, smoking; - Selection into study maybe have been related to exposure and outcome; - High attrition rate; - Weight was self-reported; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; Funding NR
Yamamoto, 2021^74^; RCS, Japan; Analytic N=17,573 (males); 8860 (females); Study objective: To assess the clinical impact of skipping breakfast, lunch, and dinner on weight gain and overweight/obesity in university students within their 6-year college life; Participant characteristics at baseline: Japanese university students; - Age: Males: 65% age 18y, 32% age 19y, 3% age ≥20y; Females: 74% age 18y, 23% age 19y, 3% age ≥20; - Female: 34%; - Race and/or ethnicity: NR, but likely majority Asian; - Socioeconomic position: All university students; - Anthropometry: BMI: males 21.6 (2.9) kg/m^2^; females 20.5 (2.4) kg/m^2^; - Physical activity: NR; - Smoking: <1% current; - TEI: NR; - Habitual diet at baseline: Eat breakfast daily: 81% males, 88% females; Skips breakfast often: 6% males, 3% females; Eat lunch daily: 94% males, 95% females; Eat dinner daily: 98% males, 96% females; Excluded from study or analysis: <18y; missing baseline data; missing body weight data during 6y observation period | Exposure: Lunch (eating every day vs skipping occasionally/often/usually); Dinner (eating every day vs skipping occasionally/often/usually); Assessment methods and timing:; - "How often did you have breakfast/lunch/dinner over the past year?"; responses were "eating almost every day", "skipping occasionally", "skipping often", and "usually skipping".; - At baseline; Outcomes and assessment methods:; - At baseline, and annually for 6y; - Weight measured during annual health exam. Incidence of weight gain ≥10% was measured in all students and incidence of overweight/obesity (BMI ≥25 kg/m^2^) was measured in students with a BMI <25 kg/m^2^. | [underlined: Weight gain ≥10%], IRR (95% CI); Males; Eating lunch every day: REF; Skipping lunch occasionally/often/usually: 1.14 (0.97, 1.35) in unadjusted models; data NR for adjusted models (figure only), NS; Females; Eating lunch every day: REF; Skipping lunch occasionally/often/usually: 0.93 (0.72, 1.20); Males; Eating dinner every day: REF; Skipping dinner occasionally/often/usually: 1.42 (1.02, 1.98); Females; Eating dinner every day: REF; Skipping dinner occasionally/often/usually: 1.67 (1.33, 2.09); [underlined: Overweight/obesity (BMI ≥25 kg/m^2^)], IRR (95% CI); Males; Eating lunch every day: REF; Skipping lunch occasionally/often/usually: data NR (figure only), NS; Females; Eating lunch every day: REF; Skipping lunch occasionally/often/usually: data NR (figure only), NS; Males; Eating dinner every day: REF; Skipping dinner occasionally/often/usually: 1.74 (1.07, 2.84); Females; Eating dinner every day: REF; Skipping dinner occasionally/often/usually: 1.68 (1.02, 2.78) | Model adjustments:; - TEI: no; - Key confounders: sex, age, anthropometry at baseline, smoking; - Other: admission year; drinking status; sleep duration on weekdays; dinner time; breakfast, lunch, and dinner frequency (e.g., breakfast frequency was adjusted for lunch and dinner frequencies); Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position, physical activity; - Exposure data only assessed at baseline leading to a concern that changes in exposure status occurred over 6y f/u; - No information on non-completers; - No preregistered data analysis plan and concerns related to selective reporting were present; - Water/Beverages were not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; No external funding

a Abbreviations: ALT: alanine aminotransferase; AST: aspartate aminotransferase; AUD: Australian Dollar; β: beta coefficient; BMI: body mass index; BMIz: body mass index z-score; BP: blood pressure; CDC: Centers for Disease Control and Prevention; CI: confidence interval; cm: centimeter(s); d: day(s); DEXA: dual energy x-ray absorptiometry; FFQ: food frequency questionnaire; g: gram(s); GGT: gamma-glutamyl transferase; HbA1c: hemoglobin A1C; HOMA-IR: Homeostatic Model Assessment of Insulin Resistance; hr: hour(s); HR: hazard ratio; IOTF: International Obesity Task Force; IQR: interquartile range; kcal: kilocalorie(s); kg: kilogram(s); lb: pound(s); m: meter(s); MET: metabolic equivalent; min: minute(s); mm: millimeter(s); MVPA: moderate to vigorous physical activity; N/A: not applicable; NCC: nested case control study; NCI: National Cancer Institute; NHLBI: National Heart, Lung, and Blood Institute; NICHD; Eunice Kennedy Shriver National Institute of Child Health and Human Development; NIDDK: National Institute of Diabetes and Digestive and Kidney Diseases; NIH: National Institutes of Health; NISOC: nmol: nanomole; NR: not reported; NS: not significant; OR: odds ratio; PCS: prospective cohort study; Project EAT: Project Eating and Activity over Time; RCS: retrospective cohort study; REF: reference group; RMB: renminbi (Chinese yuan); RR: risk ratio; SD: standard deviation; SDS: standard deviation score; SE: standard error; SEP: socioeconomic position; SES: socioeconomic status; svg: serving(s); TAG: triacylglycerol; TEI: total energy intake; wk: week(s); x: time(s); y: year(s)

Table 43 Risk of bias for observational studies examining meal frequency in adults and older adults and body composition and risk of obesity^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Chu, 2021^103^ | HIGH | HIGH | LOW | LOW | HIGH | HIGH | VERY HIGH | VERY HIGH
Larsen, 2019^80^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Odegaard, 2013^50^ | LOW* | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Phelan, 2008^52^ | HIGH | SOME CONCERNS | LOW | LOW | HIGH | HIGH | SOME CONCERNS | HIGH
Yamamoto, 2021^74^ | HIGH | SOME CONCERNS | LOW | LOW | HIGH | LOW | VERY HIGH | VERY HIGH

a Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the "Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)" tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.

Table 44 Evidence examining the relationship between meal frequency during pregnancy and gestational weight gain^a^

Study and Population Characteristics | Intervention, Comparator, and Outcome(s) | Results | Study Limitations
Samano, 2022^56^; PCS, Mexico; Analytic N=530; Study objective: To analyze whether there is an association between dietary and nutrient intake and eating habits and GWG among pregnant adolescents and their offspring’s birth weight; Participant characteristics at baseline: pregnant adolescents aged 11–19y; - Age: 15.8 (1.3)y; - Female: 100%; - Race and/or ethnicity: NR but likely majority Hispanic; - Socioeconomic position: 75% elementary education; 89% school dropout; Mostly low or very low SES; 70% single; 30% cohabitating; 89% homemakers; - Anthropometry: NR; - Physical activity: NR; - Smoking: NR; - Parity: All primigravida (inclusion criteria); - Diabetes: NR but likely none since chronic disease was an exclusion criteria; - Hypertensive Disorders: NR but likely none since chronic disease was an exclusion criteria; - TEI: 2022 (657) kcal/d; - Habitual diet at baseline: 20% had ≤2 meals/d; 56% skipped meals >1x/wk; Excluded from study or analysis: multigravida or multiple pregnancy; chronic disease; drug addictions; vegans or vegetarians; those who had a newborn with congenital malformations or stillbirth | Exposure:; Eating lunch (yes/no); eating dinner or supper (yes/no); skipping meals (never, 1–3x, or 4–5x/wk); Assessment methods and timing:; - Participants were asked about their number of meals and frequency of skipping meals (never, 1–3x/wk, 4–5x/wk); - At baseline ("during first visit", details NR); Outcomes and assessment methods:; - 1–2wk before delivery; - Gestational weight gain (GWG) calculated by subtracting self-reported initial pre-pregnancy weight from measured final gestational weight. Adequacy of GWG was based on IOM recommendations and was categorized as inadequate/insufficient (<90%), adequate (90 to <125%), and excessive (≥125%). | [underlined: GWG adequacy percentage], PR (95% CI) Inadequate; Never skipping meals: REF 1–3x/wk: 1.15 (0.85, 1.54); 4–5x/wk: 0.92 (0.57, 1.51); Excessive; Never skipping meals: REF 1–3x/wk: 0.82 (0.60, 1.12); 4–5x/wk: 1.17 (0.77, 1.77); [underlined: GWG adequacy percentage], unadjusted Chi-square; Ate lunch: 37.8% insufficient, 36.6% excessive; Skipped lunch: 0% insufficient, 33.3% excessive; p=0.047; [underlined: GWG adequacy percentage], unadjusted Chi-square; Ate dinner/supper: 36.8% insufficient, 37.3% excessive; Skipped dinner/supper: 42.9% insufficient, 31.7% excessive; p=0.591 | Model adjustments:; - TEI: no; - Key confounders: age, socioeconomic position, anthropometry at baseline, parity, diabetes mellitus in the current pregnancy, hypertensive disorders in the current pregnancy; - Other: gynecological age, antenatal care; Limitations:; - Did not account for key confounders: race and/or ethnicity, physical activity; - Exposure assessment method not validated; - Timing of exposure measurement not described; - No information on non-completers; - Outcomes were based on self-reported pre-pregnancy weight; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; - Did not adjust for TEI; Funding:; Instituto Nacional de Perinatología; CONACyT

a Abbreviations: CI: confidence interval; GWG: gestational weight gain; IOM: Institute of Medicine; NR: not reported; PCS: prospective cohort study; PR: prevalence ratio; TEI: total energy intake; wk: week(s); y: year(s)

Table 45 Risk of bias for observational study examining meal frequency in individuals during pregnancy and postpartum weight change^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Samano, 2022^56^ | HIGH | HIGH | SOME CONCERNS | LOW | HIGH | HIGH | SOME CONCERNS | VERY HIGH

a Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the "Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)" tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. )