# Results

## Literature search and screening results

The literature search was conducted to identify all potentially relevant articles for 3 systematic reviews assessing frequency of meals and/or snacking and different outcomes (alignment with the Dietary Guidelines for Americans (diet quality)^†^; energy intake^‡^; and growth, body composition, and risk of obesity), however this report is specific to the outcome of growth, body composition, and risk of obesity. The literature search (Appendix 2) yielded 31,399 search results after the removal of duplicates (see Figure 2). Dual-screening resulted in the exclusion of 27,732 titles, 2,821 abstracts, and 704 full-text articles. Reasons for full-text exclusion are in Appendix 3. No additional articles were identified from the manual search. The body of evidence on frequency of meals and/or snacking and growth, body composition, and risk of obesity included 107 articles:

- Breakfast: 75 articles^1–75^
- Snacking: 19 articles^14,15,35,45,48,50,52,57,65,76–85^
- Number of eating occasions: 24 articles^32,42,43,56,67,80,84,86–102^
- Meal frequency: 19 articles^15,45,46,50,52,54,56,69,71,74,78,80,81,84,103–107^

† Palacios C, Andres A, Odoms-Young A, . Frequency of Meals and/or Snacking and Consuming a Dietary Pattern Aligned with the Dietary Guidelines for Americans: A Systematic Review. November 2024. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.DGAC2025.SR09

‡ Andres A, Giovannucci E, Fisher JO, . Frequency of Meals and/or Snacking and Energy Intake: A Systematic Review. November 2024. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.DGAC2025.SR10

Figure 2 Literature search and screen flowchart

Literature search and screen flowchart The literature search in PubMed, Embase, Cochrane, and CINAHL retrieved 31,399 records after removing duplicates. No articles were found with manual search methods. 27,732 titles, 2821 abstracts, and 704 full-texts were excluded. 142 articles were included across the 3 systematic reviews examining frequency of meals and/or snacking. Of these, 107 articles were included in the systematic review on growth, body composition, and risk of obesity.

## Breakfast

### Description of the evidence

Seventy-five articles examined the relationship between breakfast and growth, body composition, and risk of obesity. Fifty articles were in children and adolescents^1,2,4–10,13,15–17,20–28,30,31,33–36,38–41,44–47,51,54,58–60,63,64,66,68–73^; evidence is summarized in Table 18 and risk of bias assessments for each article are detailed in Table 19 (RCT) and Table 20 (observational). Twenty-four articles were in adults and older adults^3,11,14,18,19,29,32,33,37,42,43,48–50,52,53,55,57,61,62,65,67,74,75^; evidence is summarized in Table 21 and risk of bias assessments for each article are detailed in Table 22 (RCT) and Table 23 (observational). Larson et al^33^ was included for children and adults. Two articles were in individuals during pregnancy^12,56^; evidence is summarized in Table 24 and risk of bias assessments for each article are detailed in Table 25. There were no articles examining breakfast in individuals during postpartum. Summary tables encompass each articles’ definition of breakfast consumption or skipping.

#### Children and adolescents

Among the 50 articles in children and adolescents, 1 article^28^ was a randomized controlled trial and 49 articles were from 33 observational cohorts of participants.^1,2,4–10,13,15–17,20–27,30,31,33–36,38–41,44–47,51,54,58–60,63,64,66,68–73^ Multiple articles were from the same cohort study and were included when each article reported unique data.

##### Population

The RCT was conducted in a sample of adolescents (N=105; 15.7±0.2 years old) that consumed breakfast fewer than 3 times per week.^28^ The study did not report data on socioeconomic position. At baseline, participants had a mean BMI of ~21 kg/m^2^ and ~2500 metabolic equivalent task (MET) minutes per week of physical activity.

Among the 49 observational studies, mean baseline age ranged from 2 to 16 years with 8 articles in young children (2 to 4 years);_^7,16,23,30,31,51,71,73^_ 9 in children (5 to 8 years);^5,13,23,25–27,38,41,66^ 22 in early adolescents (9 to 13 years);^1,2,4,6,8,10,15,17,20–22,24,35,41,45,46,59,60,64,68,70,72^ 13 in adolescents (14 to 18 years).^9,33,34,36,39,40,44,47,54,58,60,63,69^ While 16 articles did not report race and/or ethnicity of participants, in the articles that provided information, there was considerable representation of different race and/or ethnic backgrounds of participants. Socioeconomic position of participants was reported in 37 articles and varied across the studies. Articles included a mix of participants with normal and overweight and/or obesity at baseline with most studies including between 10–20% of participants with overweight and/or obesity.

Studies were conducted in populations from the following countries and cohorts:

- Australia: 3 articles; 1 article^30^ was secondary analysis of the Healthy Beginnings trial, 1 article^41^ from HEAPS (Health, Eating, and Play Study), and 1 article^60^ from the Childhood Determinants of Adult Health Study
- Belgium: 1 article^20^ from the Longitudinal Eating and Activity study
- Brazil: 2 articles; 1 article^8^ from an unnamed cohort and 1 article^22^ from ELANA (Adolescent Nutritional Assessment Longitudinal Study)
- China: 2 articles; 1 article^59^ was secondary analysis of the NISCOC (Nutrition based comprehensive intervention study on childhood obesity in China) trial and 1 article^64^ included data from the Hong Kong Department of Health Student Health Service.
- Germany: 5 articles; 4 articles^13,26,27,66^ were secondary analyses of the Baden-Württemberg Study cluster trial, 1 article^58^ was from the BELLA study (the module on mental health and well-being within the German Health Interview and Examination Survey for Children and Adolescents)
- Ireland: 1 article^5^ from the Childhood Obesity Surveillance Initiative
- Japan: 3 articles^23,51,73^ from the Longitudinal Survey of Newborns in the 21st Century
- South Korea: 2 articles; 1 article^28^ from an RCT and 1 article^35^ from an unnamed cohort
- Taiwan: 1 article^72^ from the Taiwan Database of Children and Youth in Poverty
- The Netherlands: 4 articles; 1 article^68^ was secondary analysis of the Dutch Obesity Intervention in Teenagers (DoiT), 1 article^31^ from the GECKO Drenthe cohort, 1 article^71^ from the Generation R study, 1 article^10^ from TRAILS (Tracking Adolescents' Individual Lives Survey)
- United Kingdom: 6 articles; 3 articles^7,25,38^ from the Millennium Cohort Study, 1 article^17^ from the DASH (Determinants of Adolescent Social wellbeing and Health) cohort, and 1 article^15^ from the Health Behaviour of School-aged Children Study
- United States: 20 articles: 1 article was secondary analysis of the TX Sprouts trial^24^, 5 articles from the National Longitudinal Study of Adolescent Health^9,36,39,44,47^, 5 articles from Project EAT (Eating and Activity over Time)^21,33,46,54,63^, 4 articles from the NHLBI Growth and Health study^1,2,4,45^, 1 article from the Growing Up Today study^6^, 1 article from the IDEA (Identifying Determinants of Eating and Activity) and ECHO (Etiology of Childhood Obesity) cohorts^34^, 1 article from the NEXT Generation Health study^40^, 1 article from Project VIVA^16^, and 1 article from an unnamed cohort^70^

##### Intervention/exposure and comparator

The RCT^28^ was a 12-week intervention in which 3 groups were compared, a rice-based breakfast, a wheat-based breakfast, and a control group that consumed a usual diet (i.e., breakfast fewer than 3 times per week). The rice- and wheat-based breakfasts provided ~760 kilocalories.

The breakfast exposure and comparators varied across the observational articles. Twenty-six articles defined breakfast intake dichotomously (yes/no),^4,5,9,10,13,16,17,23,25–27,31,36,39,41,44,45,51,64,66,69–73^ 11 articles defined it categorically,^1,6,22,24,35,38,59,60,63,69,71^ and 16 articles reported a continuous measure per week.^2,4,8,15,20,21,24,30,33,34,40,46,47,54,58,68^

Breakfast was measured mostly by questions, questionnaires, or surveys either on FFQs or alone^5–10,13,15–17,20–27,30,31,33,35,36,38–41,44,46,47,51,54,58–60,63,64,66,68–73^ (11 were identified as parent report).^5,7,13,16,25–27,31,51,66,71^. Four articles used food diaries or records^1,2,4,45^ and 1 article used 24 recalls.^34^ Seventeen of the articles only assessed breakfast intake at one time-point^5,9,13,15,26,27,35,38,39,41,45,46,58,64,66,69,73^ while 31 articles assessed breakfast intake more than 1 time^1,2,4,6,8,10,16,17,20–25,30,31,33,34,36,40,44,47,51,54,59,60,63,68,70–72^ (1 was not reported^7^).

##### Outcome

The RCT^28^ reported outcomes related to body composition and risk of obesity; all were measured by study personnel at baseline and 12-week follow-up. Body composition measures included change in fat mass, fat mass percentage, lean mass, waist circumference, and waist to hip ratio. Risk of obesity measures included change in weight, BMI, and obesity rate percentage.

Outcomes in the observational articles were measured by trained personnel or study staff in 34 articles,^1,2,4,5,7–10,13,15–17,22,24–27,30,31,34–36,38,41,45,47,58–60,64,66,68,70,71^ self/parent report (12 self-report,^6,20,21,23,33,40,44,46,54,63,72,73^ 1 parent-report^51^), and 2 articles^39,69^ measured outcomes both ways.

The outcomes that were reported varied across the observational studies:

- Risk of obesity, which included: overweight or obesity,_^5–7,9,10,23,28,30,35,41,51,70–73^_ change in BMI,^6,22,25,28,34,40,59,63,64,66,70^ overweight,^4,21,31,35,39,46,54,66^ obesity,^36,39,44,66^ BMI,^1,4,15,17,38,58,60^ change in BMI percentage,^24,66^ change in weight^13,24,28,33,66^
- Body composition, which included: body fat percentage,^8,16,38,45^ change in body fat percentage,^22,24,34,59^ waist circumference,^16,60,68^ change in waist circumference,^24,59^ fat mass percentage,^71^ trunk fat percentage,^8^ change in waist to height ratio,^27^ waist to height ratio,^17,66^ abdominal obesity,^26,66^ sum of skinfolds^68^
- Body composition, which included: change in body fat or fat mass percentage,^22,24,28,34,59^ body fat or fat mass percentage,^16,38,45,71^ change in body fat or fat mass,^8,28^ change in trunk fat mass,^8^ trunk fat mass,^16^ change in waist circumference,^24,28,59^ waist circumference,^16,60,68^ change in waist to height ratio,^27,28,59^ waist to height ratio,^17^ abdominal obesity,^26,66^ change in lean body mass,^28^ sum of skinfold thickness^68^
- Growth, which included: BMI z-scores,^2,4,16,20,41,47,68^ change in BMI z-scores,^2,5,59,66,69^ BMI standard deviations^71^

#### Adults and older adults

There were 24 articles, 2 RCTs^11,37^ and 22 observational articles^3,14,18,19,29,32,33,42,43,48–50,52,53,55,57,61,62,65,67,74,75^ from 17 prospective cohort studies^3,14,19,32,33,42,43,48–50,52,53,55,61,62,67,75^ and 5 retrospective cohort studies^18,29,57,65,74^ included in the body of evidence on breakfast intake in adults and older adults and body composition and risk of obesity.

##### Population

Three articles only included women,^3,19,42^ while 5 articles only included men;_^18,29,48,49,67^_ 4 of the articles were in young adults (in their 20s)^18,32,33,37^ and the rest ranged from 30–68 years; Most articles did not report race, and those that did were mostly conducted in the U.S. and included a majority white population. Two articles in the U.S. were about 50% White, with mostly Black and Asian populations making up the rest of the population.^33,50^ Three articles were specifically populations with overweight or obesity at baseline.^11,14,43^ There were multiple articles focused on very specific populations: 1 article was a sister study of those who had sisters with breast cancer,^19^ 2 were in college aged students,^18,19,74^ and 2 were in adults who have already had successful weight losses.^52,53^

Studies were conducted in populations from the following countries and cohorts:

- Australia: 1 article^61^ from the Childhood Determinants of Adult Health (CDAH) study
- Japan: 8 articles; 1 article^57^ from the Japan Medical Data Center Co., Ltd.; 7 unique unnamed cohorts^18,29,48,55,62,65,74^
- Mexico: 1 article_^42^_ from the Mexican Teachers’ Cohort
- Poland: 1 article^3^ which was a secondary analysis of 16-week weight loss intervention at a 1-year follow-up
- The Netherlands: 1 article^49^ from the Doetinchem Cohort Study
- United States: 10 articles; 1 article^19^ from the Sister Study, 1 article^32^ from a secondary analysis of Study of Novel Approaches to Weight Gain Prevention (SNAP) trial; 1 article^33^ from Project EAT (Eating and Activity in Teens and Young Adults); 1 article^43^ from a secondary analysis of a weight loss trial; 2 articles^52,53^ from the National Weight Control Registry; 1 article^14^ from a secondary analysis of Innovative Approaches to Diet, Exercise and Activity (IDEA) trial; 1 article^67^ from the Health Professionals Follow-up Study; 1 article^75^ from a secondary analysis of an RCT comparing AHA diet to high-fiber diet; and 1 article^50^ from Coronary Artery Risk Development in Young Adults (CARDIA).

##### Intervention/exposure and comparator

One trial randomized participants to 3 different groups: breakfast (were instructed to eat breakfast before 10am everyday), no breakfast (were told not to consume any calories before 11am) or control (receiving a pamphlet with no mention of breakfast).^11^ The second trial randomized participants to 3 groups: high protein breakfast (egg and pork-rich; 35g protein; n=24), normal protein breakfast (ready-to-eat-cereal-based; 13g protein; n=21), or continued breakfast skipping (No breakfast; n=9).^37^

The measurement and categorization of breakfast as an exposure variable varied greatly across the observational evidence. Seven studies specifically framed their exposure as breakfast skipping,^18,29,48,55,57,62,65^ 11 articles framed their exposure as breakfast frequency,^14,19,32,33,42,43,49,50,52,53,61^ while 4 articles compared eating breakfast to skipping dichotomously.^3,67,74,75^

##### Outcome

The outcomes reported in the intervention studies were change in weight^11^ and lean mass, fat mass, body fat%, BMI, and weight.^37^

Outcomes were measured by trained personnel or study staff, at annual health visit, or by self-report.

The outcomes that were reported varied across the observational studies:

- Risk of obesity: change in weight, weight gain/regain/maintenance, incidence of overweight and/or obesity change in BMI
- Body composition: change in fat mass, abdominal obesity, change in waist circumference, waist to height ratio

#### Individuals during pregnancy and postpartum

Both articles examining breakfast in individuals during pregnancy were prospective cohort studies.^12,56^

##### Population

One study was secondary analysis of the Starting Early Child Obesity Prevention trial conducted in the U.S.^12^ The study was conducted in a sample of low-income Hispanic women during pregnancy (N=508, 63% <30 years of age). The majority of women had a pre-pregnancy BMI in the overweight/obesity categories and 55% met physical activity recommendations prior to pregnancy. The study did not report data on family history of diabetes or hypertensive disorders.

The other study was conducted in a sample of Mexican pregnant adolescents (N=530; 15.8±1.3 years old).^56^ Most (75%) participants had an elementary education and 89% dropped out of school. The study did not report data on baseline anthropometry, physical activity, or family history of diabetes or hypertensive disorders.

##### Intervention/exposure and comparator

One article asked participants during the third trimester whether they consumed breakfast on a daily basis (as part of a FFQ assessing intake during the previous 12 months).^56^ The second article asked participants during their first prenatal visit whether they skipped breakfast (yes/no).^56^

##### Outcome

Both articles calculated gestational weight gain (GWG) by subtracting self-reported initial pre-pregnancy weight from measured final gestational weight. Adequacy of GWG was based on 2009 Institute of Medicine recommendations and was categorized as inadequate/insufficient, adequate, and excessive.

### Synthesis of the evidence

#### Children and adolescents

Among the 50 articles in children and adolescents, 1 article^28^ was a randomized controlled trial and 49 articles were from 33 observational cohorts of participants.^1,2,4–10,13,15–17,20–27,30,31,33–36,38–41,44–47,51,54,58–60,63,64,66,68–73^ While articles varied in how they described the breakfast exposure the synthesis is framed to address breakfast consumption compared to not consuming breakfast or consuming breakfast less frequently. This was discussed as the most appropriate framing for this population.

##### Interventions

In Kim and colleagues^28^, the group that consumed a wheat-based breakfast had a significantly higher change in fat mass percentage compared to the control group that consumed breakfast fewer than 3 times per week; adolescents that consumed a wheat-based breakfast increased fat mass by 0.1±2.4 percent over 12 weeks, whereas the control group decreased fat mass. There were no significant differences between the breakfast groups and the control group that consumed breakfast fewer than 3 times per week for change in fat mass, lean mass, waist circumference, waist to hip ratio, weight, BMI, or obesity rate percentage.

##### Observational studies

Twenty-nine of the 49 observational articles reported that consuming breakfast was significantly associated with at least one favorable outcome related to growth, body composition, and/or lower risk of obesity, compared to not consuming breakfast or consuming breakfast less often.^2,8,9,16,17,20,21,23,26,27,33,36,38,39,41,44–46,51,54,58,60,64,66,70,71^

Additionally, 17 of the 49 articles reported no statistically significant associations between breakfast consumption and growth, body composition, or risk of obesity outcomes.^1,4,7,10,13,15,24,30,31,34,35,40,59,60,63,68,69^ However, the majority of the articles’ results trend in the direction of a positive relationship between breakfast consumption and favorable outcomes. Additionally, 1 article reported on BMI trajectory and reported results in both directions and was not highly considered in the synthesis because the interpretation of the results was not clear.

Only one study looked at breakfast consumption in childhood and followed the participants into adulthood.^60^ While they also had exposure measures as adults, only the breakfast measures from childhood were considered here. They reported that participants who skipped breakfast as a child and adult had higher BMI and waist circumference at 21y follow-up compared to those who did not skip breakfast as a child or adult, however, this result was null when comparing participants who only skipped breakfast as a child compared to those who did not skip breakfast as a child or an adult.

Only two of the observational articles reported that less breakfast consumption compared to more breakfast consumption per week was associated with unfavorable growth, body composition, or risk of obesity outcomes.^6,22^ One article reported that children who were with overweight and never ate breakfast was associated with lower BMI over the following year compared to children who were with overweight and ate breakfast every day; whereas children who were normal weight and never ate breakfast was associated with gaining weight over the same timepoint compared to children who were normal weight and ate breakfast almost every day.^6^ The second article reported that girls who consumed breakfast 1–4 days per week had lower increases in body fat percentage over 3 years compared to those that ate breakfast ≥5 days per week.^22^ However, there was no association among boys and breakfast frequency was not related to change in BMI for either sex.

Results were further assessed by sex, adjustment for total energy intake, categorization of breakfast, and baseline weight status, however, none of these factors helped to explain the inconsistencies of statistical significance and direction in this body of evidence.

#### Adults and older adults

There were 24 articles, 2 RCTs^11,37^ and 22 observational articles^3,14,18,19,29,32,33,42,43,48–50,52,53,55,57,61,62,65,67,74,75^ from 17 prospective cohort studies^3,14,19,32,33,42,43,48–50,52,53,55,61,62,67,75^ and 5 retrospective cohort studies^18,29,57,65,74^ included in the body of evidence on breakfast in adults and older adults and body composition and risk of obesity.

##### Interventions

Both included trials were interpreted as contributing null results:

- There was no difference in weight change over 16 weeks between participants who were randomized to eat breakfast compared to those who did not eat breakfast.^11^
- In a trial in nonhabitual breakfast eating young adults with overweight/obesity, those who consumed a high-protein breakfast had decreased fat mass and body fat percentage compared to those who did not eat breakfast during a 12-week trial.^37^ However, there was no difference in lean mass, BMI, or weight and this trial was interpreted as having mixed results due to the body of evidence including outcomes of BMI and weight more frequently.

##### Observational studies

The measurement and categorization of breakfast as an exposure variable varied greatly across the evidence. In order to synthesize the results, all reported comparisons were reoriented to focus on breakfast skipping to be most applicable to the topic that this systematic review is tasked under (which is strategies for individuals and families related to diet quality and weight management). While the definition of breakfast skipping varied across studies, this review considers breakfast skipping as consuming breakfast less than 7 days per week and was being compared to more frequent consumption of breakfast.

Only one observational article^49^ reported that breakfast skipping was associated with lower waist circumference, a body composition outcome, and no articles reported that breakfast skipping was associated with favorable weight or BMI nor a decrease in overweight or obesity rates compared to eating breakfast more frequently. One study was conducted in men (mean age ~56 years) and although they reported an association with waist circumference, they reported no association with weight in the same population.^49^

The remaining 21 observational articles reported either null associations or reported that breakfast skipping was associated with unfavorable body composition and risk of obesity outcomes.^3,14,18,19,29,32,33,42,43,48,50,52,53,55,57,61,62,65,67,74,75^ Fourteen of the articles reported at least one association between breakfast skipping and an unfavorable measure or change in fat mass,^14^ waist circumference,^55^ abdominal obesity,^50,57^ weight,^3,14,32,42,43,53,61,67^ BMI,^18,55,65^ and overweight^29^ or obesity.^50,57^ Six articles reported no association between breakfast skipping and body composition or risk of obesity outcomes.^33,48,52,62,74,75^ One article reported that both eating breakfast everyday as well as breakfast skipping were both associated with favorable outcomes, and therefore was interpreted as a null finding.^19^ While not statistically significant, most associations trended in the direction of results consistent with the rest of the body of evidence.

Results were further assessed by sex, adjustment for total energy intake, categorization of breakfast, and baseline weight status, however, none of these factors helped to explain the inconsistencies of statistical significance in this body of evidence.

Most of the studies were in younger adults, however there was representation from older participants in multiple studies and therefore adults and older adults are included within this body of evidence supporting one conclusion statement.

#### Individuals during pregnancy and postpartum

One article found that eating breakfast daily was associated with lower risk of inadequate GWG.^56^ Another article found no association between skipping breakfast and adequacy of GWG.^56^ Both studies did not adjust for total energy intake. Conclusion statements and grades were not developed for breakfast in pregnancy or postpartum because there was not enough evidence available. A Grade Not Assignable conclusion statement was developed for overall frequency of eating during pregnancy and gestational weight gain and overall frequency of eating and postpartum weight change (Table 16 and Table 17).

### Conclusion statements and grades

The 2025 Dietary Guidelines Advisory Committee developed conclusion statements for the systematic review question: “What is the relationship between frequency of meals and/or snacking and growth, body composition, and risk of obesity?” based on their review of evidence on breakfast in children and adolescents (Table 5) and adults and older adults (Table 6).

Table 5 Conclusion statement and grade for breakfast in children and adolescents and growth, body composition, and risk of obesity

Conclusion Statement | Regular breakfast consumption by children and adolescents may be associated with favorable outcomes related to growth, body composition, and/or lower risk of obesity. This conclusion statement is based on evidence graded as moderate.
Grade | Moderate
Body of Evidence | 50 articles: 1 RCT; 49 observational
Consistency | Some concerns with inconsistency of significance of results and inconsistency in comparators being assessed.
Precision | Few concerns with sample size/power and variance.
Risk of bias | Serious concerns with definition and measurement of exposures as well as concerns with confounding, missing data, and selection of reported results.
Directness | Some concerns, particularly with comparators of the exposure.
Generalizability | Few concerns with generalizability to the U.S. population.

#### Assessment of the evidence

The body of evidence underlying the conclusion statement in children and adolescents included 50 articles, 1 intervention study and 49 observational articles from 32 unique cohorts or trial groups. While more intervention studies are preferred, the difficulty in designing and funding studies on this exposure is acknowledged due to ethical concerns with restricting consumption of or access to breakfast for this age group. The evidence was graded based on an assessment of five grading elements, as described below. Publication bias was also considered but there were few concerns since the body of evidence includes both large and small studies, including small studies with null findings. There is further risk of publication bias because a search of gray literature was not conducted.

##### Consistency

The direction of findings was generally consistent across the body of evidence in that children and adolescents who ate breakfast were associated with favorable outcomes compared to those who did not eat breakfast, however about one-third of the associations in this direction were not statistically significant. Comparators within the studies were inconsistent with most studies assessing breakfast consumption dichotomously, but others using continuous and varied categories. While this inconsistency was acknowledged, differences in comparators did not explain variation in the results across articles.

##### Precision

There was only one intervention study contributing to this conclusion statement, and there were many observational articles with generally large sample sizes. Magnitude of results were generally small which may have led to null findings that were not adequately powered. Secondary data analysis from trial data was used in 7 articles from unique 5 trials and it was noted that these analyses may have a stronger causal effect than purely observational analyses.

##### Risk of bias

There were serious concerns with numerous risks of bias domains, which may potentially influence the results that were reported in the articles. Across the body of evidence, the measurement of breakfast consumption was particularly concerning as it was not well defined and was subject to measurement error. The comparators used across the studies were inconsistent and reasons for the choice of comparator were generally not discussed in the articles. There were also concerns with confounding since many articles from observational studies did not account for anthropometry at baseline or physical activity. Many articles had issues with missing data and did not provide evidence that their results were not biased. Lastly, the selection of reported results was a concern especially those articles without pre-registered data analysis plans.

##### Directness

The one intervention study that contributed to this evidence does not directly answer the question given that they were assessing breakfast consumption in habitual breakfast skippers and were comparing a rice-based and wheat-based breakfast to usual diet. While all of the observational articles directly assessed breakfast consumption, there were some concerns with varied comparisons (e.g. dichotomous, continuous, categorical) leading to methodological heterogeneity in the body of evidence that may have resulted in inconsistencies in the significance of the results.

##### Generalizability

Studies were conducted primarily in the U.S. and had broad representation across racial and or ethnic groups and socioeconomic positions. While this result is generalizable to the U.S. population, it is noted that specific breakfast foods, contents, or quality were not able to be considered in this review.

Table 6 Conclusion statement and grade for breakfast in adults and older adults and body composition and risk of obesity

Conclusion Statement | Breakfast skipping in adults and older adults is not associated with favorable outcomes related to body weight and composition and risk of obesity. This conclusion statement is based on evidence graded as limited.
Grade | Limited
Body of Evidence | 24 articles: 2 RCTs and 22 observational
Consistency | Serious concerns with consistency of significant results
Precision | Serious concerns, particularly with small sample sizes
Risk of bias | Serious concerns, particularly due to confounding and definition and measurement of the exposures
Directness | Few concerns in the directness of interventions, exposures, comparators, and outcomes
Generalizability | Some concerns with the applicability of results to the U.S. population

#### Assessment of the evidence

The body of evidence underlying the conclusion statement in adults and older adults included 24 articles (2 RCTs and 22 articles from observational studies). The evidence was graded based on an assessment of five grading elements, as described below. Although publication bias is always a concern, this body of evidence includes both large and small studies, including small studies with null findings, so there are few concerns of publication bias. There is further risk of publication bias because a search of gray literature was not conducted.

##### Consistency

Significance of results across the body of evidence varied leading to concerns with consistency. However, while statistical significance was inconsistent, only 1 article reported that breakfast skipping was associated with favorable body composition outcomes. Twenty-three out of 24 articles consistently support that breakfast skipping was not associated with favorable body weight or composition and risk of obesity.

##### Precision

Magnitude of results were generally small which may have led to null findings that were not adequately powered. However, sample sizes were generally adequate and ranged from 64 to 123,182 participants in the observational studies.

##### Risk of bias

There were serious concerns with numerous risks of bias domains, which may potentially influence the results that were reported in the articles. Across the body of evidence, the measurement of breakfast consumption was particularly concerning as it was not well defined and was subject to measurement error based on only measuring breakfast at baseline. The comparators used across the studies were inconsistent and reasons for the choice of comparator were generally not discussed in the articles. There were also concerns with confounding since many articles from observational studies did not account for anthropometry at baseline or physical activity. Many articles had issues with missing data and did not provide evidence that their results were not biased. Lastly, the selection of reported results was a concern especially those articles without pre-registered data analysis plans.

##### Directness

The body of evidence directly answers the question on breakfast and body composition and risk of obesity outcomes. While all the observational articles directly assessed breakfast consumption, there were some concerns with varied comparisons (e.g., dichotomous, continuous, categorical) leading to methodological heterogeneity in the body of evidence that may have resulted in inconsistencies in the significance of the results.

##### Generalizability

While the included trial data was not very generalizable to the U.S. population, the 22 observational studies were more representative of various race and/or ethnic groups, and participants of different socioeconomic positions. The articles tended to focus on young adults, and some included older adults.

## Snacking

### Description of the evidence

Nineteen articles examined the relationship between snacking and growth, body composition, and risk of obesity. Seven articles were in children and adolescents^15,35,45,78,79,81,84^; evidence is summarized in Table 26 and risk of bias assessments for each article are detailed in Table 27. Twelve articles were in adults and older adults^14,48,50,52,57,65,76,77,80,82,83,85^; evidence is summarized in Table 28 and risk of bias assessments for each article are detailed in Table 29 (RCT) and Table 30 (observational). There were no articles examining snacking in individuals during pregnancy or postpartum. Summary tables encompass each articles definition of snacking.

#### Children and adolescents

All 7 articles examining snacking in children and adolescents were prospective cohort studies.

##### Population

Studies were conducted in the following countries: South Korea^35,78,81^, UK^15^, and United States^40,45,79,84^. The mean baseline age ranged from 3 to 12 years. Sample sizes ranged from N=93 to N=26,047. Among studies conducted in the U.S., 1 article^79^ was conducted in all White girls; and 2 articles^45,84^ enrolled an even distribution of Black and White girls. Five articles were diverse in terms of parental education or income^45,78,79,81,84^ and 2 articles^15,35^ did not report data on socioeconomic position. Studies generally included participants across BMI weight status categories.

##### Intervention/exposure and comparator

Three articles examined snacking frequency as a dichotomous variable (i.e., yes or no).^35,45,81^ Four articles examined snacking frequency as a continuous variable (i.e., number of snacks consumed per day, times per day).^15,78,79,84^ Most articles examined snacking frequency at baseline only; one article^79^ measured snacking frequency at multiple timepoints. Two articles^45,84^ from the NHLBI Growth and Health Study used 3-day food records, 2 articles used three 24-hour recalls,^79,81^ and 2 articles used a nutrition questionnaire.^15,78^ One article asked children a single question about the number of night snacking.^35^

##### Outcome

No articles examined growth. Two articles^45,84^ from the NHLBI Growth and Health Study examined body composition obtained from standard measures. One article^45^ measured body fat percentage from sum of skinfolds and another article^84^ measured waist circumference.

Six articles examined risk of obesity, and they all used measured height and weight.^15,35,78,79,81,84^ Four articles^15,79,81,84^ examined BMI, 1 article^78^ examined incidence of obesity, and 1 article^35^ examined weight status as a categorical variable.

#### Adults and older adults

Eleven articles^14,48,50,52,57,65,76,77,80,82,85^ examining snacking in adults and older adults were observational studies and 1 article^83^ was a parallel randomized controlled trial.

##### Population

The trial had a mean baseline age of 40 years and the analytic sample sizes of study groups was N=100.^83^ Participants were 27% White, 40% African American, 3% Asian, and 30% Hispanic; 63% had at least some college education. The trial had inclusion criteria for BMI 25–30 kg/m^2^.

Among observational studies, mean baseline age ranged from 30 to 68 years. One study^65^ was conducted in participants with a mean age ≥60 years and 1 study^48^ enrolled only males. Studies in the United States reported data on race and/or ethnicity and were as follows: 82% White, 15% Black, 3% Asian^14^; 96% Caucasian^52^; 54% White and 46% Black^50^; 77% White, 3% Black, 10% Asian, 5% Hispanic/Latino, 3% Other.^76^ Participants were generally diverse in terms of participant education and/or income level; 2 studies^65,85^ from Japan did not report data on socioeconomic position. Studies generally included participants across BMI weight status categories.

##### Intervention/exposure and comparator

One trial evaluated snacking in the context of a structured meal replacement program.^83^ All participants were provided with coupons every 2 weeks for Slim Fast shakes, meal bars, and snack bars and were required to consume a minimum of 2 Slim Fast products a day. In the snacking group, participants were told to use the Slim Fast products for meals and their 3 snacks a day. This was in comparison to a non-snacking group in which participants were told to use the Slim Fast products for meals and were explicitly encouraged to not use any snacks and to avoid excess calories between meals.

Most observational studies examined snacking as a dichotomous variable (e.g., yes/no, non vs usual). Four articles examined snacking as a continuous variable (e.g., days per week or times per day).^50,52,76,80^

##### Outcome

Outcomes included body composition and risk of obesity:

- Eight articles examined body composition, which included: abdominal obesity,^50,55,57,85^ change in waist circumference,^33,57,80^ waist circumference,^76,82^ change in body fat percentage,^80^ change in fat mass,^14,80^ change in lean mass,^14^ and change in waist to hip ratio^65^
- Eleven articles examined risk of obesity, which included: obesity,^48,50,57,77,85^ change in weight,^14,52,77,83^ change in BMI,^65,80^ and BMI^76^

### Synthesis of the evidence

#### Children and adolescents

Five out of 7 articles reported that there was no association between snacking and body composition and risk of obesity outcomes.^15,35,78,79,84^ Of these, 2 articles^15,79^ looked at number of snacks as a continuous, times per day measure, 2 articles^78,84^ looked at number of snacks per day categories comparing >3 or ≥3 snacks per day to categories <3 times per day, and 1 article^35^ looked specifically at dichotomous frequent night snacking (yes/no).

Two other articles reported mixed results within each article when assessing different categories of the exposure and within specific sub-populations:

- In the NHLBI cohort, snacking in the afternoon or evening compared to not snacking (i.e., analyzed dichotomously as yes/no) was associated with lower body fat percentage in Black and White adolescent girls at a 10-year follow-up.^45^ This association was null when looking at morning snacking.
- Snacking compared to not snacking was associated with an increase in BMI in 10-year-olds (4th grade) children over a 2-year follow-up, but there was no change in BMI in 7-year old (1st grade) children.^81^

#### Adults and older adults

##### Interventions

In a meal replacement weight loss trial, there was no difference in weight loss at 12 weeks or 24 weeks between participants randomized to snacks and a meal replacement compared to those randomized to a meal replacement only.^83^

##### Observational studies

There were 11 observational articles included in the body of evidence on snacking and body composition and risk of obesity in adults and older adults. However, there was a lot of variation in the exposures that were included with 7 articles^48,50,52,76,77,80,82^ reporting overall snacking or snacking at other times of the day and 6 articles^14,50,57,65,76,85^ reporting after dinner or evening snacking. The following observational studies were synthesized based on those categories of the snacking.

###### Overall snacking

This exposure varied, including measuring any snacking (yes/no), number of snacks per day (continuous or categorical), and number of snacks by time of day (e.g., mid-morning, afternoon, evening). In most studies, it was not possible to determine what time of day the snacks were consumed. The term “overall snacking” will be used to describe this variable.

When looking at overall snacking, 4 of 7 articles reported null results when assessing snacking throughout the day, in the morning, or mid-day and body composition and risk of obesity in adults.^50,52,76,82^ Larsen et al^80^ did report a positive association between snacking frequency and higher change in fat mass index and body fat percentage; however, results were null in regard to change in waist circumference and change in BMI over a 6-year follow-up. Two other articles that assessed snacking dichotomously reported that adults who reported snacking compared to adults who did not report snacking had an increase in obesity or in weight over 3- and 4-year follow-ups.^48,77^

Two of the above articles assessed morning and afternoon/mid-day snacking, which was indicative of overall snacking without the influence of after dinner or evening snacking.^50,76^ Both of these articles reported no association between morning snacking and afternoon/mid-day snacking and body composition and risk of obesity outcomes.

###### After dinner or evening snacking

When isolating the 6 articles that only looked at snacking after dinner or in the evening, there was a much more consistent association between snacking at this time and less favorable body composition and risk of obesity outcomes.^14,50,57,65,76,85^ Four of the 6 articles reported at least one association between after dinner or evening snacking and increases in fat mass,^14^ waist circumference,^76^ weight,^14^ BMI,^76^ or obesity.^57,85^ The significant results reported in Yoshida et al^85^ were only in males and the same association was not reported in female participants.

The classification of the overall snacking exposure includes evening snacking which could be contributing to the inconsistency in the findings, potentially driving results away from the null. The findings should be interpreted together, with context from both contributing to the evidence on snacking in adults.

It is important to note that the types and quality of the snacking being consumed was not available. There is potential that this difference in timing of snacking may be driven by a difference in quality of snacks being consumed at different times throughout the day.

Only one of the articles^65^ had a mean age of >60 years and therefore the evidence was only generalizable to adults. A grade not assignable conclusion statement was formed for the relationship between snacking and body composition and risk of obesity in older adults.

### Conclusion statements and grades

The 2025 Dietary Guidelines Advisory Committee developed conclusion statements for the systematic review question: “What is the relationship between frequency of meals and/or snacking and growth, body composition, and risk of obesity?” based on their review of evidence on snacking in children and adolescents (Table 7), adults (Table 8), and older adults (Table 9).

Table 7 Conclusion statement and grade for snacking in children and adolescents and growth, body composition, and/or risk of obesity

Conclusion Statement | Frequency of daily snacking during childhood may not be associated with outcomes related to growth, body composition, and/or risk of obesity. This conclusion statement is based on evidence graded as limited.
Grade | Limited
Body of Evidence | 7 articles: observational
Consistency | Few concerns with inconsistency in the results
Precision | Some concerns, particularly with small sample sizes
Risk of bias | Serious concerns, particularly with confounding, definition and misclassification of exposures
Directness | Some concerns, particularly with definition and categorization of the exposure as well as quality of snacks not being assessed
Generalizability | Serious concerns with generalizability of results to the U.S. population due to lack of representation of race and/or ethnic groups and different socioeconomic positions

#### Assessment of the evidence

The body of evidence underlying the conclusion statement in children and adolescents included 7 articles from observational studies. The evidence was graded based on an assessment of five grading elements, as described below. Although publication bias is always a concern, this body of evidence includes both large and small studies, including small studies with null findings, so there are few concerns of publication bias. There is further risk of publication bias because a search of gray literature was not conducted.

##### Consistency

The body of evidence was very consistent in that the majority of articles reported evidence of no relationship between snacking during childhood and body composition and risk of obesity. The 2 articles that reported significant findings were in a sub-population within a study or for snacking at a specific time of day.

##### Precision

Precision across the articles was adequate in that sample sizes ranged from 93 to 26,047 and power was not identified as a concern for why these studies were null.

##### Risk of bias

Risk of bias concerns were identified throughout this body of evidence. Missing data was a large concern given that the articles did not provide evidence that the results were not due to missing data. All but one of the articles didn’t account for at least one key confounder in their analyses. Additionally, there were concerns with the snacking exposure in that it was generally not well defined and at risk for measurement error because it was generally only measured at baseline. There were also some concerns with the selection of reported results.

##### Directness

While all the articles did directly answer the systematic review question, based on the exposure and the outcomes, the comparators varied greatly across the articles lowering the ability for the articles to be easily compared. Snacking was compared dichotomously, continuously, and categorically, as well as snacking at specific times of day.

##### Generalizability

The body of evidence only included a small number of observational studies leading to a lack of generalizability. Two of the 7 articles were from the same cohort of participants and the majority of articles were from outside the United States, with 3 of 7 articles from South Korea.

Table 8 Conclusion statement and grade for snacking in adults and body composition and risk of obesity

Conclusion Statement | Overall snacking in adults may not be associated with outcomes related to body composition and risk of obesity. However, after dinner/evening snacking in adults may be associated with less favorable outcomes related to body composition and risk of obesity. This conclusion statement is based on evidence graded as limited.
Grade | Limited
Body of Evidence | 12 articles: 1 RCT; 11 observational
Consistency | Some concerns with inconsistent direction of effects
Precision | Serious concerns, particularly with small sample sizes in overall snacking and some concerns for overall snacking
Risk of bias | Serious concerns with confounding, exposure misclassification, and selection of reported results
Directness | Some concerns, particularly with varied exposures that did not assess quality of snacks
Generalizability | Serious concerns with generalizability due to few studies

#### Assessment of the evidence

The body of evidence underlying the conclusion statement in adults included 12 articles (1 RCT and 11 articles from observational studies). The evidence was graded based on an assessment of five grading elements, as described below. Although publication bias is always a concern, this body of evidence includes both large and small studies, including small studies with null findings, so there are few concerns of publication bias. There is further risk of publication bias because a search of gray literature was not conducted.

##### Consistency

There was general consistency in the direction and significance of the results for after dinner or evening snacking and body composition and risk of obesity outcomes. The direction was less consistent for the overall snacking exposure; however, the null findings were supported by the one included randomized controlled trial. This inconsistency may have been due to the measurement of overall snacking, including counts of snacking after dinner or in the evening.

##### Precision

There were serious concerns with precision in the articles reporting on overall snacking due to small sample sizes ranging from 257 to 10,162 participants in the observational studies and fewer concerns with precision in the articles reporting on after dinner or evening which included the RCT with 100 participants which was adequately powered.

##### Risk of bias

Various risks of bias were identified across the body of evidence. Specifically, there were major issues with articles not providing evidence that the results were not impacted by missing data and pre-registered data analysis plans were not found. There were also issues with the measurement of snacking, not defining it well or being subject to measurement error because information was only collected at baseline. All but 2 of the articles did not adjust for at least one key confounder such as race and/or ethnicity and physical activity.

##### Directness

While the exposures and outcomes directly answered the systematic review question on snacking and body composition and risk of obesity outcomes in adults, the comparators varied widely throughout the body of evidence. The overall snacking exposure was measured dichotomously, continuously, and categorically, while also including specific timing of snacking in the morning and afternoon snacking.

##### Generalizability

There are many issues with generalizability of the results being mostly based on younger adult populations (30 to 50 years) and only 4 of 11 the articles being from the U.S. with 4 of the other articles based in Japan. Additionally, there were too few studies and not enough trial data to support the observational findings.

Table 9 Conclusion statement and grade for snacking in older adults and body composition and risk of obesity

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between snacking in older adults and body composition and risk of obesity because there is not enough evidence available.
Grade | Grade Not Assignable
Body of Evidence | 1 article
Rationale | There is not enough evidence available to answer this question.

## Number of eating occasions

### Description of the evidence

Twenty-four articles examined the relationship between number of eating occasions and growth, body composition, and risk of obesity. Eight articles were in children and adolescents^84,86,88,90,94,98–100^; evidence is summarized in Table 31 and risk of bias assessments are detailed in Table 32. Thirteen articles were in adults and older adults^32,42,43,67,80,87,89,91,92,96,97,101,102^; evidence is summarized in Table 33 and risk of bias assessments are detailed in Table 34 (RCT) and Table 35 (observational). One article^56^ was in individuals during pregnancy (Table 36) and 2 articles^93,95^ were in individuals during postpartum (Table 37); risk of bias assessments for each article are detailed in Table 38 and Table 39. Summary tables encompass each articles definition of number of eating occasions.

#### Children and adolescents

All 8 articles examining number of eating occasions in children and adolescents were observational studies. Four of the 8 articles were secondary analyses of trial data, which were identified as a stronger study design.^86,90,94,99^

##### Population

Studies were conducted in the following countries: New Zealand^99^, Peru^88^, Spain^86,94^, UK^98^, and United States^84,90,100^. The mean baseline age ranged from 2 to 11 years. Sample sizes ranged from N=81 to N=2,146. Studies that reported data on race and/or ethnicity were as follows: 96% White^98^; 74% White and 26% Other^100^; 89% New Zealand European, 6% Maori, 5% Asian^99^; 49% White and 51% Black^84^; 44% White, 12% Black, 15% Asian, 11% Hispanic, 20% Other^90^; 73% with Spanish-origin mother.^86^ For socioeconomic position, all studies provided data on parental education. Three studies provided additional data on income.^88,90,100^

Articles included participants across BMI weight status categories. Two articles were exclusively in females,^84,100^ while the other 6 articles included both sexes. The mean ages of participants ranged from 2 to 11 years at baseline of the studies.

##### Intervention/exposure and comparator

All articles examined number of eating occasions as a continuous variable (i.e., times per day). Four articles provided definitions for eating occasion, which was generally defined as an eating event separated by ≥15 minutes.^86,90,98,100^ Most articles examined number of eating occasions at baseline only. Two studies examined measured number of eating occasions at multiple time-points.^88,100^ Most studies measured the number of eating occasions using a 2- to 7-day diet record.^84,98–100^ Two studies used 24-hour recalls,^86,90^ 1 study used a parent questionnaire,^88^ and 1 study^94^ had children respond whether they consumed a mid-morning snack or afternoon snack (yes/no).

##### Outcome

Five articles examined growth (e.g., BMI z-scores or weight gain)^90,94,98–100^; all but 1 study^98^ measured outcomes collected by study personnel. Three articles examined body composition (e.g., abdominal obesity, fat mass index, waist circumference, waist-to-height ratio) using standard measures.^84,86,94^ Three articles examined risk of obesity (e.g., BMI, risk of overweight or obesity) using measured height and weight.^84,88,94^

#### Adults and older adults

There were 13 articles included that assessed number of eating occasions in adults and body composition and risk of obesity.^32,42,43,67,80,87,89,91,92,96,97,101,102^ Five are RCTs^87,89,92,101,102^ and ^8^ are observational studies.^32,42,43,67,80,91,96,97^ Of the ^8^ observational studies, 3 were secondary analysis of trial data.^32,43,97^

##### Population

Among trials, mean baseline age ranged from 30 to 51 years. Analytic sample sizes of study groups among the trials ranged from N=40 to N=93. Three trials did not report data on race and/or ethnicity or socioeconomic position^89,92,101^; one article^102^ did not report data on race and/or ethnicity but reported that 61% of participants had academic degrees. Another trial^87^ was 94% White, 6% Black, and 98% non-Hispanic, and was diverse in terms of participant education level. All trials included participants with overweight and/or obesity.

Among observational studies, mean baseline age ranged from 28 to 57 years. Analytic sample sizes ranged from N=20 to N=65,099. Out of the 5 articles from the U.S.,^32,43,67,96,97^ 4 reported information on race and/or ethnicity of which 3 had populations that were >70% White,^32,43,97^ while the other reported that 78% of participants identified as a racial or ethnic minority with 45% of the populations reporting that they were Hispanic.^96^ The other 3 articles were conducted in Mexico,^42^ Denmark,^80^ and Greece.^91^ Across studies, there was a diverse range of socioeconomic position reported, with regard to education or employment. Most observational studies included participants with a mixed range of baseline weight status, with 2 articles that only included participants with overweight or obesity at baseline.^43,97^

##### Intervention/exposure and comparator

Most trials compared 3 meals per day to 6 meals per day under hypocaloric conditions. The intervention details are as follows:

- Bachman et al^87^: Both groups participated in a standard behavioral intervention for reducing obesity for 6 months. The 6-meal group was provided with instructions to “graze” by eating at least 100 kcal every 2 to 3 hours (~6 eating bouts per day at 3- and 6-months: 3 meals and 3 snacks). The 3-meal group was provided with instructions to eat 3 meals per day (~3 eating bouts per day at 3- and 6-months: 3 meals). Participants defined meals and snacks, which were only counted if at least 25 kilocalories were consumed. All foods and beverages eaten within 30 minutes of the start of a meal/snack were counted as a single eating bout. Eating frequency equaled the number of meals, snacks, and total eating bouts (meals + snacks) reported in the food records.
- Forslund and colleagues^89^: The 6-meal group divided daily energy intake into breakfast (20%), lunch (25%), dinner (25%) and 3 snacks (10% each). The 3-meal group divided daily energy intake into breakfast (30%), lunch (35%) and dinner (35%); no snacks were allowed with the exception of limited fruit intake and calorie-free drinks.
- Grangeiro et al^92^: The 6-meal group divided total energy expenditure into breakfast (15%), snack (5–10%), lunch (25%), snack (5–10%), dinner (25%) and evening snack (5–10%). The 3-meal group divided total energy expenditure into breakfast (20–25%), lunch (35–40%), and dinner (35–40%). The diets had the same macronutrient distribution. Diets were reduced 500–1000 kilocalories per day to obtain body weight reduction of 2–4 kilograms per month. Breakfast, lunch and dinner were defined to provide more than 15% of the total energy expenditure and the snacks provided less than 15%.
- Yildiran et al^101^: All participants were on a weight loss diet. The 6-meal group ate breakfast, lunch, dinner, and 3 snacks. The 3-meal group ate breakfast, lunch, and dinner.
- Zargaran et al^102^: All participants were on a weight loss diet. The 6-meal group ate 6 isocaloric meals (one meal every 3 hours) compared to the control group that consumed the usual diet (usually 5 meals: 3 main meals and 2 snacks).

Among the observational articles, 5 reported number of eating occasions per day (times per day) as a continuous measure,^32,43,80,96,97^ and 3 reported it as categorical.^42,67,80,91^ The categories used were different in each of the 3 articles: 1–2, 3–4, ≥5 times/d^42^; 3, 4, ≥5 times/day^67^; and ≤5 vs >5 times/day as well as quartiles.^91^ Three articles only measured the exposure at baseline.^42,67,91,96^ Methods used to measure number of eating occasions were generally measured by surveys or questionnaires and both the time periods being assessed (e.g., last 7 days, last 30 days), as well as the questions asked to participants varied.

##### Outcome

Outcomes included body composition and risk of obesity:

- Six articles examined body composition measures, which included: fat-free mass,^87,92,101^ fat mass,^92,101^ change in waist circumference,^80,91,92^ change in fat mass,^80,92^ change in fat-free mass,^92^ change in body fat percentage,^80^ waist circumference,^92,96,101^ and maximum preperitoneal and arm fat thickness^91^
- All 13 articles examined at least one measure for risk of obesity, which included: BMI,^87,91,92,96,101,102^ change in weight,^32,42,67,92,97^ change in BMI,^80,92^ percentage change in weight,^43,97^ and weight^92,101^

#### Individuals during pregnancy and postpartum

All 3 articles examining number of eating occasions in individuals during pregnancy and postpartum were prospective cohort studies.^56,93,95^

##### Population

One study was conducted in individuals during pregnancy, specifically a Mexican sample of pregnant adolescents (N=530; 15.8±1.3 years old).^56^ Most (75%) participants had an elementary education and 89% dropped out of school. The study did not report data on baseline anthropometry, physical activity, or family history of diabetes or hypertensive disorders.

Two studies were conducted in individuals during postpartum.^93,95^ One article examined a sample of postpartum women (N=687; 31.3±5.2 years old) from the GUSTO (Growing Up in Singapore towards Healthy Outcomes) cohort.^95^ Women were of Chinese, Malay, or Indian descent; 33% had a tertiary education and 67% were employed. Most (66%) were mixed feeding, 25% were formula feeding, and 9% were breast feeding. The second article was a secondary analysis of the LEVA (Lifestyle for effective weight loss during lactation) trial in a Swedish sample of women (N=60; 33.2±4.1 years old). Most (72%) women had more than 3 years education beyond high school.^93^ Almost all participants were exclusively breastfeeding.

##### Intervention/exposure and comparator

In the article conducted in individuals during pregnancy, participants were asked about their number of meals per day (<2, 3, or >3) during the first prenatal visit.^56^

Among articles conducted in individuals during postpartum, 1 article used a 24-hour recall at baseline for collecting data on number of eating episodes (defined as events that provided ≥50 kcal in intervals of ≥15 minutes); the number of eating occasions was categorized into 4 groups (≤3, 4, 5, and ≥6 times per day).^95^ The second article used a 4-day diet record to assess change in the mean number of intake occasions per day over 12 weeks; an intake occasion was defined as an energy intake of ≥50 kcal, including foods and/or beverages, separated in time from the preceding and following intake occasion by at least 30 minutes.^93^

##### Outcome

The article in individuals during pregnancy calculated GWG by subtracting self-reported initial pre-pregnancy weight from measured final gestational weight.^56^ Adequacy of GWG was based on 2009 Institute of Medicine recommendations and was categorized as inadequate/insufficient, adequate, and excessive.

One article calculated postpartum weight retention (PPWR) by subtracting measured weight at the first antenatal visit (≤14 weeks gestation) and measured weight at 18 months postpartum; women were categorized into non-substantial PPWR (<5 kg) and substantial PPWR (≥5 kg).^95^ Another article calculated change in postpartum weight by measuring weight at 10–14 weeks postpartum and at 22–26 weeks postpartum (after the 12-week intervention).^93^

### Synthesis of the evidence

#### Children and adolescents

Four articles reported significant inverse associations between number of eating occasions per day and growth, body composition, and risk of obesity outcomes, in that greater number of eating occasions per day was associated with favorable outcomes.^84,88,94,100^

- One article was conducted in children from a poor area in Peru and reported that those with ≤4 eating occasions per day had increased BMI and BMI z-scores compared to those with 5 eating occasions a day.^88^
- The second article reported that girls who ate 4.0-5.9 times per day had smaller increases in BMI z-scores over 6 years compared to girls who ate ≥6 times per day.^100^
- Ritchie, 2012^84^ reported that among black and white female adolescents, a higher initial total eating frequency was associated with smaller 10-year increases in waist circumference and BMI.
- The last article reported that among children participating in a community-based childhood obesity prevention intervention, higher meal frequency was associated with lower BMI z-scores, abdominal obesity, waist-to-height ratio, and odds of overweight/obesity.^94^

Two articles reported that there was no association between number of eating occasions and growth, body composition outcomes.^86,99^ One article^86^ was a secondary analysis of trial data and only the results within the control group of the trial were considered in order to isolate the impact of the exposure however, this did not change the interpretation of the articles results.

Two articles reported a positive association between number of eating occasions per day and growth outcomes. One article^90^ reported an initial association between higher daily eating frequency and increased BMI z-scores at a 6-month follow-up; however, this was no longer significant at 1-year follow-up. The other article^98^ that reported a positive association was in a population of preschool children in which each extra meal per day increased weight gain by 1 gram per week; however, this was only significant when meal size was held constant.

#### Adults and older adults

##### Interventions

All 5 trials were developed in a weight-loss context only including participants with overweight or obesity.^87,89,92,101,102^ They all provided hypocaloric diets to participants, and they controlled for energy intake across the trial arms.

Four of the 5 trials compared 6 versus 3 eating occasions per day and all reported that there was no significant effect of number of eating occasions on body composition or risk of obesity outcomes.^87,89,92,101^. The other trial^102^ did report that 6 isocaloric meals every 3 hours lead to a decrease in BMI compared to those who ate a “usual diet” of 5 eating occasions (3 meals and 2 snacks).

##### Observational studies

Six of 8 observational articles reported that there was no association between number of eating occasions per day in adults and risk of obesity outcomes including change in weight^32,43,97^ or BMI.^80,91,96^ One of these studies did report that number of eating occasions was associated with increases in measures of pre-peritoneal fat (Pmax) and abdominal fat index (AFI) and no changes in waist circumference, and BMI, which were weighed more heavily in the synthesis because of their use to estimate risk of obesity.^91^

Two articles reported that a higher number of eating occasions per day in adults was associated with an increase in weight^42,67^ and weight gain.^42^ Both articles assessed number of eating occasions as a categorical variable as where the articles with null findings assessed it continuously. Additionally, both of these studies used self-reported weight outcomes in their analysis as where the studies with null findings all measured outcomes using study staff or clinic visits. While these 2 articles had large sample sizes, the magnitude of the results were small.

It is of note that the 3 articles that were secondary analyses of trial data all reported no association between number of eating occasions per day in adults and risk of obesity. These analyses may be stronger and better able to directly answer the systematic review question given the trial conditions and methodology.

None of the included articles had participants with a mean age of >60 years and therefore is only generalizable to adults and not to older adults. A grade not assignable conclusion statement was formed for the relationship between number of eating occasions and body composition and risk of obesity in older adults.

#### Individuals during pregnancy and postpartum

There was no association between number of eating occasions and adequacy of GWG.^56^ The study did not adjust for total energy intake.

Both studies in individuals during postpartum found no association between number of eating occasions and postpartum weight change.^93,95^ Both studies adjusted for total energy intake. Conclusion statements and grades were not developed for number of eating occasions in pregnancy or postpartum because there was not enough evidence available. A Grade Not Assignable conclusion statement was developed for overall frequency of eating during pregnancy and gestational weight gain and overall frequency of eating and postpartum weight change (Table 16 and Table 17).

### Conclusion statements and grades

The 2025 Dietary Guidelines Advisory Committee developed conclusion statements for the systematic review question: “What is the relationship between frequency of meals and/or snacking and growth, body composition, and risk of obesity?” based on their review of evidence on number of eating occasions in children and adolescents (Table 10), adults (Table 11), and older adults (Table 12).

Table 10 Conclusion statement and grade for number of eating occasions in children and adolescents and growth, body composition, and/or risk of obesity

Conclusion Statement | Higher number of eating occasions per day during childhood may be associated with favorable outcomes related to growth, body composition, and/or lower risk of obesity. This conclusion statement is based on evidence graded as limited.
Grade | Limited
Body of Evidence | 8 articles: observational
Consistency | Some inconsistency in significance or the results.
Precision | Some concerns, particularly with small sample sizes.
Risk of bias | Serious concerns, particularly with confounding, exposure measurement, and missing data.
Directness | Some concerns, particularly with directness of exposure and varied comparators used.
Generalizability | Serious concerns with generalizability to the U.S. population due to few studies, majority outside of U.S.

#### Assessment of the evidence

The body of evidence underlying the conclusion statement in children and adolescents included 8 articles from observational studies. The evidence was graded based on an assessment of five grading elements, as described below. Although publication bias is always a concern, this body of evidence includes both large and small studies, including small studies with null findings, so there are few concerns of publication bias. There is further risk of publication bias because a search of gray literature was not conducted.

##### Consistency

The results were relatively inconsistent in significance, but were generally consistent in direction, although the magnitude of the effects were generally small across the body of evidence. In the two articles that reported inconsistent findings, they were either no longer significant at a subsequent follow-up or were controlling for meal size.

##### Precision

Precision in the articles was limited with small sample sizes across the body of evidence ranging from N=81 to N=2,146.

##### Risk of bias

There were many risk of bias issues identified. There were major issues with articles not providing evidence that the results were not impacted by missing data and pre-registered data analysis plans were not found. There were also issues with the measurement of number of eating occasions, not defining it well or being subject to measurement error because information on exposure was only collected at baseline. More than half of the studies did not adjust for key confounders including race and/or ethnicity and physical activity.

##### Directness

Articles directly answered the question of number of eating occasions per day and its impact on growth, body composition, and risk of obesity outcomes. However, the comparators varied across the studies leading to difficulty in the interpretation of the articles together.

##### Generalizability

There were serious concerns with the generalizability of the studies included in this body of evidence. The majority of studies were not conducted in the U.S. and even thought there were articles included that had representation of various race and/or ethnicities, there were not enough studies with varied study designs included for the populations to be generalizable.

Table 11 Conclusion statement and grade for number of eating occasions in adults and body composition and risk of obesity

Conclusion Statement | Number of eating occasions per day in adults is not associated with outcomes related to change in body composition and weight. This conclusion statement is based on evidence graded as moderate.
Grade | Moderate
Body of Evidence | 13 articles: 5 RCTs, 8 observational
Consistency | Few concerns with consistency in the direction and significance of results
Precision | Some concerns, particularly with sample size
Risk of bias | Serious concerns, particularly due to confounding, missing data, and selection of reported results
Directness | Few concerns in the directness of interventions, exposures, comparators, and outcomes
Generalizability | Some concerns due to the trials being in a weight loss context and the observational studies in younger adults

#### Assessment of the evidence

The body of evidence underlying the conclusion statement in adults included 13 articles (5 articles from RCTs and 8 articles from observational studies). The evidence was graded based on an assessment of five grading elements, as described below. Although publication bias is always a concern, this body of evidence includes both large and small studies, including small studies with null findings, so there are few concerns of publication bias. There is further risk of publication bias because a search of gray literature was not conducted.

##### Consistency

There was consistency in the lack of relationship between number of eating occasions per day in adults and body composition and weight across the trials, secondary analyses of trial data, and observational articles. When articles were inconsistent, there was generally a difference in study methodology that may have explained the difference. The magnitude of the effects of those studies was small.

##### Precision

The precision across the body of evidence was limited and ranged from 20 to 65,099 participants.

##### Risk of bias

Various risks of bias were identified across the body of evidence. Specifically, there were major issues with articles not providing evidence that the results were not impacted by missing data and pre-registered data analysis plans were not found for observational articles. There were also issues with number of eating occasions being subject to measurement error in observational articles because information was only collected at baseline. All but 1 observational article did not adjust for at least one key confounder such as race and/or ethnicity and smoking.

##### Directness

The studies directly answered the question on number of eating occasions and body composition and risk of obesity. There were limitations with the comparators used across studies (continuous vs various categories)

##### Generalizability

The trials were not particularly generalizable to the U.S. population given that they were all weight loss trials in participants with overweight or obesity, however, when combined with the observational studies the body of evidence was representative of the U.S. population in terms of race and/or ethnicity and socioeconomic position. The conclusion statement is only generalizable to adults and not older adults.

Table 12 Conclusion statement and grade for number of eating occasions in older adults and body composition and risk of obesity

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between number of eating occasions in older adults and body composition and risk of obesity because there is not enough evidence available.
Grade | Grade Not Assignable
Body of Evidence | 0 articles
Rationale | There is not enough evidence available to answer this question.

## Meal frequency

### Description of the evidence

Nineteen articles examined the relationship between meal frequency and growth, body composition, and risk of obesity. Thirteen articles were in children and adolescents^15,45,46,54,69,71,78,81,84,104–107^; evidence is summarized in Table 40 and risk of bias assessments are detailed in Table 41. Five articles were in adults and older adults^50,52,74,80,103^; evidence is summarized in Table 42 and risk of bias assessments are detailed in Table 43. One article was in individuals during pregnancy^56^; evidence is summarized in Table 44 and the risk of bias assessment is detailed in Table 45. There were no articles examining meal frequency in individuals during postpartum. Summary tables encompass each articles definition of meal frequency.

#### Children and adolescents

All 13 articles examining meal frequency in children and adolescents were prospective cohort studies.

##### Population

Studies were conducted in the following countries: Norway^107^, South Korea^78,81^, The Netherlands^71^, UK^15,69^, and the United States^45,46,54,84,104–106^. The mean baseline age ranged from 3 to 17 years. Sample sizes ranged from N=355 to N=26,047. Among studies in the U.S., data on race and/or ethnicity was as follows: 1 article^104^ was predominately White, 3 articles^45,84,105^ from the NHLBI Growth and Health study enrolled an even distribution of Black and White girls, and 3 articles^46,54,106^ from Project EAT had enrollment of 50% White, 18% Black, 19% Asian, 6% Hispanic, 4% Other, and 3% Native American adolescents. Seven articles^45,71,78,81,84,104,107^ were diverse in terms of participant education and/or income levels and 6 articles^15,46,54,69,105,106^ did not report data on socioeconomic position. Studies included participants across BMI weight status categories.

##### Intervention/exposure and comparator

Eight articles examined meal frequency (including skipping).^71,78,81,84,104–107^ Five articles examined dinner frequency (i.e., days per week, or a categorical measure of frequency).^15,46,54,69,71^ Five articles examined lunch frequency.^15,45,46,54,71^ Most articles used a questionnaire to measure meal frequency.^15,69,71,78,104,107^ Three articles^46,54,106^ from Project EAT measured meal frequency using a single question and 3 articles^45,84,105^ from the NHLBI Growth and Health Study used 3-day food records. Lee et al^81^ used three 24-hour recalls.

##### Outcome

Three articles examined growth, and all were BMI z-scores.^69,71,105^ Viner et al^69^ examined change in BMI z-scores from adolescence to adulthood using self-reported measure of height and weight. Two studies examined BMI z-scores calculated from measured height and weight.^71,105^

Three articles examined body composition.^45,71,84^ One article^71^ examined fat mass percentage obtained from dual-energy X-ray absorptiometry (DEXA) and another article^45^ examined body fat percentage obtained from sum of skinfold measurements. One article examined change in waist circumference measured by trained examiners.^84^

Eleven articles examined risk of obesity.^15,46,54,71,78,81,84,104–107^ Six articles examined incidence of overweight and/or obesity^46,54,71,78,105,107^. Most articles determined BMI weight status categories from measured height and weight; 2 articles^46,54^ assessed incidence of overweight and/or obesity from self-reported height and weight. Four articles examined BMI^15,81,84,106^; all but 1 article^106^ calculated BMI from measured height and weight. One article examined change in self-reported weight.^104^

#### Adults and older adults

All 5 articles examining meal frequency in adults and older adults were observational studies (4 PCS, 1 RCS).

##### Population

Studies were conducted in the following countries: Denmark^80^, Japan^74^, and the United States^50,52,103^. Mean baseline age ranged from 19 to 46 years. Sample sizes ranged from N=257 to N=17,573. Three studies from the U.S. reported data on race and/or ethnicity: 96% Caucasian^52^; 54% White and 46% Black^50^; 68% non-Hispanic White, 16% non-Hispanic Black, 12% Hispanic/Latino, 3% non-Hispanic Asian/Pacific Islander, 1% American Indian/Native American, 1% Other.^103^ All studies provided some measure of socioeconomic position (i.e., education or household income). BMI at baseline ranged from 21 to 26 kg/m^2^.

##### Intervention/exposure and comparator

Three studies examined lunch and dinner frequency (i.e., days per week, or a categorical measure of frequency) based on a single question or questionnaire.^50,52,74^ One study examined meal frequency based on a survey of the number of meals eaten during the day and frequency of snacking between meals.^80^ One study examined whether participants engaged in specific behaviors to lose or maintain weight, including fasting or skipping meals.^103^

##### Outcome

Two studies examined body composition obtained from standard measures.^50,80^ One article^50^ examined incidence of abdominal obesity and another article^80^ examined 6-year change in fat mass index, fat-free mass index, body fat percentage, and waist circumference.

Five studies examined risk of obesity.^50,52,74,80,103^ Most studies measured height and weight using standard measures; two studies^52,103^ used self-reported measures. Two studies examined change in BMI.^80,103^ Two studies examined incidence of overweight and/or obesity^50,74^ or incidence of weight gain ≥10%^74^. One article examined change in self-reported weight over 2–3 months (from pre-holiday to post-holiday, and from pre-holiday to 1 month after the holiday).^52^

#### Individuals during pregnancy and postpartum

The article examining meal frequency in individuals during pregnancy was a prospective cohort study in a Mexican sample of 530 pregnant adolescents (15.8±1.3 years old).^56^ Most (75%) participants had an elementary education and 89% dropped out of school. The study did not report data on baseline anthropometry, physical activity, or family history of diabetes or hypertensive disorders. Participants were asked during their first prenatal visit about their frequency of skipping meals (never, 1–3 times per week, 4–5 times per week) and eating lunch or supper/dinner (yes vs no). Gestational weight gain (GWG) was calculated by subtracting self-reported initial pre-pregnancy weight from measured final gestational weight (1–2 weeks before delivery). Adequacy of GWG was based on IOM recommendations and was categorized as inadequate/insufficient (<90%), adequate (90 to <125%), and excessive (≥125%). There was no evidence in the postpartum period.

### Synthesis of the evidence

#### Children and adolescents

Among studies that examined growth outcomes, 1 study^69^ found no association between lunch frequency and BMI z-scores and 2 studies^69,71^ found no association between evening/dinner meal frequency and BMI z-scores. Franko et al^105^ found that participants who ate ≥3 meals on more days had lower BMI z-scores.

Among studies that examined body composition outcomes, 1 study^71^ found no association between lunch frequency and fat mass percentage and 1 study^45^ found that skipping lunch was associated with higher body fat percentage. One study^71^ found no association between dinner frequency and fat mass percentage and 1 study found^84^ no association between meal frequency and change in waist circumference.

Out of 11 articles that examined risk of obesity outcomes, 7 reported no association between meal frequency (including lunch or dinner) or skipping with change in weight, change in BMI, or risk of overweight or obesity.^15,46,71,78,81,104,107^ In Project EAT, meal skipping was associated with greater change in BMI in both boys and girls^106^; lunch and dinner frequency was associated with higher odds of having overweight in boys and dinner frequency was associated with lower odds of having overweight in girls.^54^ One article^105^ found that Black girls who ate ≥3 meals on more days had a lower odds of having overweight; there was no association in White girls. Ritchie, 2012^84^ found that higher meal frequency was associated with greater change in BMI.

#### Adults and older adults

Among studies that examined body composition outcomes, most findings were null. One article^50^ found no association between lunch or dinner frequency with abdominal obesity when adjusting for total energy intake.^50^ Another article found no association between meal frequency at baseline or 5-year change in meal frequency with change in fat-free mass index, body fat percentage, or waist circumference; meal frequency at baseline was associated with lower change in fat mass index, and this was no longer significant among a subsample with adjustment for total energy intake.^80^

Among studies that examined risk of obesity outcomes, 3 reported no association between lunch frequency and weight gain or risk of obesity.^50,52,74^ Two studies^50,52^ found no association between dinner frequency and change weight gain or risk of obesity, and 1 study^74^ found that skipping dinner every day was associated with a higher risk of weight gain and overweight/obesity. One study^80^ found that men with BMI <18.5 kg/m^2^ (underweight) who fasted or skipped meals in order to lose/maintain weight was associated with increased BMI at 7- and 15-year follow-up; there was no association between fasting/skipping meals and change in BMI in women (regardless of BMI) or men with BMI >18.5 kg/m^2^. Another study found that higher meal frequency (at baseline and 5-year change) was associated with decreased BMI at 6-year follow-up.^80^

#### Individuals during pregnancy and postpartum

There was no association between lunch frequency, dinner/supper frequency, or skipping meals with adequacy of GWG.^56^ The study did not adjust for total energy intake. Conclusion statements and grades were not developed for meal frequency in pregnancy or postpartum because there was not enough evidence available. A Grade Not Assignable conclusion statement was developed for overall frequency of eating during pregnancy and gestational weight gain and overall frequency of eating and postpartum weight change (Table 16 and Table 17).

### Conclusion statements and grades

The 2025 Dietary Guidelines Advisory Committee developed conclusion statements for the systematic review question: “What is the relationship between frequency of meals and/or snacking and growth, body composition, and risk of obesity?” based on their review of evidence on meal frequency in children and adolescents (Table 13 and Table 14) and adults and older adults (Table 15).

Table 13 Conclusion statement and grade for meal frequency in children and adolescents and risk of obesity

Conclusion Statement | Meal frequency/skipping by children and adolescents may not be associated with outcomes related to risk of overweight or obesity. This conclusion statement is based on evidence graded as limited.
Grade | Limited
Body of Evidence | 11 articles: observational
Consistency | Some concerns with inconsistency in direction and significance of results
Precision | Some concerns with small sample sizes
Risk of bias | Serious concerns, particularly with confounding, exposure misclassification, and selection of reported results.
Directness | Serious concerns, particularly with the heterogeneity of exposures
Generalizability | Serious concerns with generalizability to the U.S. population due to few studies, majority outside of U.S.

#### Assessment of the evidence

The body of evidence underlying the conclusion statement for risk of obesity in children and adolescents included 11 articles from observational studies. The evidence was graded based on an assessment of five grading elements, as described below. Although publication bias is always a concern, this body of evidence includes both large and small studies, including small studies with null findings, so there are few concerns of publication bias. There is further risk of publication bias because a search of gray literature was not conducted.

##### Consistency

The results were generally consistent and while there were some inconsistencies in the direction and significance of findings, these inconsistencies were all within articles reporting data from the same cohort of participants.

##### Precision

Precision in the articles was adequate across the body of evidence with sample sizes ranging from N=355 to N=26,047.

##### Risk of bias

Various issues were identified related to risk of bias in the included articles. There was particular concern with selection of reported results and exposure misclassification since inconsistent findings were all from the same cohort of participants who were reporting different analyses of the data. There were also major issues with articles not providing evidence that the results were not impacted by missing data. Another major concern was in the measurement of meal frequency, not defining it well or being subject to measurement error because information on exposure was only collected at baseline. More than half of the studies did not adjust for at least one identified key confounder.

##### Directness

There were serious concerns with the directness of the associations supporting this conclusion statement. Meal frequency varied in how it was defined: meal frequency or skipping (7 articles), lunch frequency or skipping (4 articles), and dinner frequency or skipping (4 articles). There was also a lot of variation in the comparators across the articles leading to difficulty in the interpretation of the articles together.

##### Generalizability

There were serious concerns with generalizability to the U.S. population due to so few studies with no included trials. While 6 out of the 11 articles were from the U.S., these articles were only from 3 unique cohorts of participants.

Table 14 Conclusion statement and grade for meal frequency in children and adolescents and growth and body composition

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between meal frequency/skipping by children and adolescents and growth and body composition because there is not enough evidence available.
Grade | Grade Not Assignable
Body of Evidence | 5 articles – observational
Rationale | There were not enough studies that reported results in relation to growth and body composition, and therefore a conclusion statement could not be drawn.

Table 15 Conclusion statement and grade for meal frequency in adults and older adults and body composition and risk of obesity

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between lunch or dinner frequency in adults and older adults and outcomes related to body composition and risk of obesity because of substantial concerns related to directness and generalizability in a small body of evidence.
Grade | Grade Not Assignable
Body of Evidence | 5 articles – observational
Rationale | The evidence available to answer this question had high variability in the exposures and were unable to be synthesized together.

## Frequency of meals and/or snacking during pregnancy and gestational weight gain

Two articles examined frequency of meals and/or snacking in individuals during pregnancy and gestational weight gain.^12,56^ As discussed earlier in the systematic review, both articles examined breakfast, 1 article^56^ examined number of eating occasions, and 1 article^56^ examined meal frequency.

### Conclusion statement and grade

The 2025 Dietary Guidelines Advisory Committee was not able to develop a conclusion statement to answer the question “What is the relationship between frequency of meals and/or snacking and growth, body composition, and risk of obesity?” based on their review of evidence in individuals during pregnancy and gestational weight gain (Table 16).

Table 16 Conclusion statement and grade for frequency of meals and/or snacking during pregnancy and gestational weight gain

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between frequency of meals and/or snacking during pregnancy and gestational weight gain because there is not enough evidence available.
Grade | Grade Not Assignable
Body of Evidence | 2 articles: observational
Rationale | There is not enough evidence available to answer this question. One article was in adolescents.

## Frequency of meals and/or snacking during postpartum and postpartum weight change

Two articles examined frequency of meals and/or snacking in individuals during postpartum and postpartum weight change.^93,95^ As discussed earlier in the systematic review, both articles examined number of eating occasions.

### Conclusion statement and grade

The 2025 Dietary Guidelines Advisory Committee was not able to develop a conclusion statement to answer the question “What is the relationship between frequency of meals and/or snacking and growth, body composition, and risk of obesity?” based on their review of evidence in individuals during postpartum and postpartum weight change (Table 17).

Table 17 Conclusion statement and grade for frequency of meals and/or snacking during postpartum and postpartum weight change

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between frequency of meals and/or snacking during postpartum and postpartum weight change because there is not enough evidence available.
Grade | Grade Not Assignable
Body of Evidence | 2 articles: observational
Rationale | There is not enough evidence available to answer this question.