# Plain language summary

### What is the question?

The question is: What is the relationship between frequency of meals and/or snacking and growth, body composition, and risk of obesity? The populations of interest for this question include children and adolescents (1 up to 19 years), adults and older adults (19 years and older), and individuals during pregnancy and postpartum.

### Why was this question asked?

This systematic review was conducted by the 2025 Dietary Guidelines Advisory Committee as part of the process to develop the Dietary Guidelines for Americans, 2025–2030.

### How was this question answered?

The Committee conducted a systematic review to answer this question with support from the USDA Nutrition Evidence Systematic Review team.

### What is the answer to the question?

#### Breakfast

- Regular breakfast consumption by children and adolescents may be associated with favorable outcomes related to growth, body composition, and/or lower risk of obesity. This conclusion statement is based on evidence graded as moderate.
- Breakfast skipping in adults and older adults is not associated with favorable outcomes related to body weight and composition and risk of obesity. This conclusion statement is based on evidence graded as limited.

#### Snacking

- Frequency of daily snacking during childhood may not be associated with outcomes related to growth, body composition, and/or risk of obesity. This conclusion statement is based on evidence graded as limited.
- Overall snacking in adults may not be associated with outcomes related to body composition and risk of obesity. However, after dinner/evening snacking in adults may be associated with less favorable outcomes related to body composition and risk of obesity. This conclusion statement is based on evidence graded as limited.
- A conclusion statement cannot be drawn about the relationship between snacking in older adults and body composition and risk of obesity because there is not enough evidence available.

#### Number of eating occasions

- Higher number of eating occasions per day during childhood may be associated with favorable outcomes related to growth, body composition, and/ or lower risk of obesity. This conclusion statement is based on evidence graded as limited.
- Number of eating occasions per day in adults is not associated with outcomes related to change in body composition and weight. This conclusion statement is based on evidence graded as moderate.
- A conclusion statement cannot be drawn about the relationship between number of eating occasions in older adults and body composition and risk of obesity because there is not enough evidence available.

#### Meal frequency

- Meal frequency/skipping by children and adolescents may not be associated with outcomes related to risk of overweight or obesity. This conclusion statement is based on evidence graded as limited.
- A conclusion statement cannot be drawn about the relationship between meal frequency/skipping by children and adolescents and growth and body composition because there is not enough evidence available.
- A conclusion statement cannot be drawn about the relationship between lunch or dinner frequency in adults and older adults and outcomes related to body composition and risk of obesity because of substantial concerns related to directness and generalizability in a small body of evidence.

#### Frequency of meals and/or snacking

- A conclusion statement cannot be drawn about the relationship between frequency of meals and/or snacking during pregnancy and gestational weight gain because there is not enough evidence available.
- A conclusion statement cannot be drawn about the relationship between frequency of meals and/or snacking during postpartum and postpartum weight change because there is not enough evidence available.

### How up-to-date is this systematic review?

Conclusion statements from this review are based on articles published between January 2000 and May 2023.