# Appendix 3 Excluded articles

The following table lists the articles excluded after full-text screening for this systematic review question. At least one reason for exclusion is provided for each article, though this may not reflect all possible reasons. Information about articles excluded after title and abstract screening is available upon request.

Table A 6 Articles excluded after full-text screening

| Citation | Rationale
1 | [No authors listed]. Skipping meals might increase the risk of metabolic syndrome. Article. Nature Clinical Practice Endocrinology and Metabolism. 2008;4(10):532–533. doi:10.1038/ncpendmet0934 | Study design; Publication status
2 | [No authors listed]. Virchow and the Weight-loss Breakfast. Orthopedics. Jun 1 2009;32(6):397. doi:10.3928/01477447-20090511-03 | Study design
3 | Abdullatif M, Alabady K, Altheeb A, Rishmawi F, Jaradat H, Farooq S. Prevalence of Overweight, Obesity, and Dietary Behaviors among Adolescents in Dubai Schools: A Complex DesignSurvey 2019. Article. Dubai Medical Journal. 2022;5(1):1–9. doi:10.1159/000519863 | Study design
4 | Abildso CG, Schmid O, Byrd M, Zizzi S, Quartiroli A, Fitzpatrick SJ. Predictors of weight loss maintenance following an insurance-sponsored weight management program. J Obes. 2014;2014:736080. doi:10.1155/2014/736080 24738027 | Study design
5 | Agras WS, Hammer LD, McNicholas F, Kraemer HC. Risk factors for childhood overweight: a prospectivestudy from birth to 9.5 years. J Pediatr. Jul 2004;145(1):20–5. doi:10.1016/j.jpeds.2004.03.023 | Intervention/Exposure
6 | Agyeppong A, Selfridge N. Time-Restricted Eating, Weight Loss, and Metabolism. Internal Medicine Alert. 2021;43(5):1–3. | Intervention/Exposure; Publication status
7 | Ahmad N, Shariff ZM, Mukhtar F, Lye M-S. Family-based intervention using face-to-face sessions and social media to improve Malay primary school children's adiposity: a randomized controlledfield trial of the Malaysian REDUCE programme. Nutr J. 2018;17(1):N.PAG-N.PAG. doi:10.1186/s12937-018-0379-1 | Intervention/Exposure
8 | Ainscough KM, Kennelly MA, Lindsay KL, An observational analysis of meal patterns in overweight and obese pregnancy: exploring meal pattern behaviours and the association with maternal and fetal health measures. Ir J Med Sci. May 2020;189(2):585–594. doi:10.1007/s11845-019-02099-0 31732868 | Outcome
9 | Aizawa M, Murakami K, Takahashi I, Association between frequency of breakfast intake before and during pregnancy and infant birth weight: the Tohoku Medical Megabank Project Birth and Three-Generation Cohort Study. BMC Pregnancy Childbirth. Apr 19 2023;23(1):268. doi:10.1186/s12884-023-05603-8 37076802 | Outcome
10 | Aksungar FB, Sarikaya M, Coskun A, Serteser M, Unsal I. Comparison of Intermittent Fasting Versus Caloric Restriction in Obese Subjects: A Two Year Follow-Up. J Nutr Health Aging. 2017;21(6):681–685. doi:10.1007/s12603-016-0786-y 28537332 | Intervention/Exposure
11 | Aksungar FB, Topkaya AE, Akyildiz M. Interleukin-6, C-reactive protein and biochemical parameters during prolonged intermittent fasting. Ann Nutr Metab. 2007;51(1):88–95. doi:10.1159/000100954 17374948 | Intervention/Exposure
12 | Al-Ardhi GH, Ibraheem NJ, Al-Maamory AM, Abd-Alameer AM. Comparison of some physiological parameters determined by timing consumption of breakfast meal among adult women. Article. Indian Journal of Forensic Medicine and Toxicology. 2021;15(3):2394–2396. doi:10.37506/ijfmt.v15i3.15670 | Study design; Intervention/Exposure
13 | Al-Rawi N, Madkour M, Jahrami H, Effect of diurnal intermittent fasting during Ramadan on ghrelin, leptin, melatonin, and cortisol levels among overweight and obese subjects: A prospectiveobservational study. PLoS One. 2020;15(8):e0237922. doi:10.1371/journal.pone.0237922 32845924 | Intervention/Exposure
14 | Albertson AM, Affenito SG, Bauserman R, Holschuh NM, Eldridge AL, Barton BA. The relationship of ready-to-eat cereal consumption to nutrient intake, blood lipids, and body mass indexof children as they age through adolescence. J Am Diet Assoc. Sep 2009;109(9):1557–65. doi:10.1016/j.jada.2009.06.363 19699835 | Intervention/Exposure
15 | Aldhoon-Hainerova I, Hainer V, Zamrazilova H. Impact of dietary intake, lifestyle and biochemical factors on metabolic health in obese adolescents. Nutr Metab Cardiovasc Dis. Aug 2017;27(8):703–710. doi:10.1016/j.numecd.2017.05.002 28693964 | Study design
16 | Alencar MK, Beam JR, McCormick JJ, Increased meal frequency attenuates fat-free mass lossesand some markers of health status with a portion-controlled weight loss diet. Journal article. Nutrition Research. May 2015;35(5):375–383. doi:10.1016/j.nutres.2015.03.003 25862614 | Outcome; Duration
17 | Alexy U, Wicher M, Kersting M. Breakfast trends in children and adolescents: frequency and quality. Public Health Nutr. Nov 2010;13(11):1795–802. doi:10.1017/S1368980010000091 20236559 | Intervention/Exposure; Outcome
18 | Alhussain MH, Macdonald IA, Taylor MA. Irregular meal-pattern effects on energy expenditure, metabolism, and appetite regulation: a randomized controlled trial in healthy normal-weight women. Am J Clin Nutr. Jul 2016;104(1):21–32. doi:10.3945/ajcn.115.125401 27305952 | Outcome; Duration; Other
19 | Alinezhad-Namaghi M, Eslami S, Nematy M, Intermittent Fasting During Ramadan and Its Effects in Individuals With Metabolic Syndrome. Nutrition Today. 2019;54(4):159–164. doi:10.1097/NT.0000000000000351 | Intervention/Exposure
20 | Allirot X, Saulais L, Seyssel K, An isocaloric increase of eating episodes in the morning contributes to decrease energy intake at lunch in lean men. Journal article. Physiology & Behavior. Feb 17 2013;110:169–178. doi:10.1016/j.physbeh.2013.01.009 23333553 | Intervention/Exposure
21 | Allirot X, Seyssel K, Saulais L, Effects of a breakfast spread out over time on the food intakeat lunch and the hormonal responses in obese men. Physiol Behav. Mar 29 2014;127:37–44. doi:10.1016/j.physbeh.2014.01.004 24472321 | Intervention/Exposure
22 | Allison KC, Hopkins CM, Ruggieri M, Prolonged, Controlled Daytime versus Delayed EatingImpacts Weight and Metabolism. Curr Biol. Feb 8 2021;31(3):650–657 e3. doi:10.1016/j.cub.2020.10.092 33259790 | Intervention/Exposure; Comparator
23 | Almeneessier AS, BaHammam AA, Alzoghaibi M, Olaish AH, Nashwan SZ, BaHammam AS. The effects of diurnal intermittent fasting on proinflammatory cytokine levels while controlling for sleep/wake pattern, meal composition and energy expenditure. PLoS One. 2019;14(12):e0226034. doi:10.1371/journal.pone.0226034 31821377 | Intervention/Exposure
24 | Almeneessier AS, Bahammam AS, Sharif MM, The influence of intermittent fasting on the circadian pattern of melatonin while controlling for caloric intake, energy expenditure, light exposure, and sleep schedules: A preliminary report. Article. Annals of Thoracic Medicine. Jul-Sep 2017;12(3):183–190. doi:10.4103/atm.ATM_15_17 28808490 | Intervention/Exposure
25 | Almoosawi S, Prynne CJ, Hardy R, Stephen AM. Time-of-day and nutrient composition of eating occasions: prospective association with the metabolic syndrome in the 1946 British birth cohort. Int J Obes (Lond). May 2013;37(5):725–31. doi:10.1038/ijo.2012.103 22777542 | Intervention/Exposure
26 | Almoosawi S, Prynne CJ, Hardy R, Stephen AM. Time-of-day of energy intake: association with hypertension and blood pressure 10 years later in the 1946 British Birth Cohort. J Hypertens. May 2013;31(5):882–92. doi:10.1097/HJH.0b013e32835ecc06 23385650 | Intervention/Exposure; Outcome
27 | Alqaoud N, Al-Jawaldeh A, Al-Anazi F, Subhakaran M, Doggui R. Trend and Causes of Overweightand Obesity among Pre-School Children in Kuwait. Children (Basel). Jun 19 2021;8(6)doi:10.3390/children8060524 | Study design
28 | Alsharairi NA, Somerset SM. Skipping breakfast in early childhood and its associations with maternal and child BMI: a study of 2–5-year-old Australian children. Eur J Clin Nutr. Apr 2016;70(4):450–5. doi:10.1038/ejcn.2015.184 26508462 | Intervention/Exposure; Outcome
29 | Alviso-Orellana C, Estrada-Tejada D, Carrillo-Larco RM, Bernabe-Ortiz A. Sweetened beverages, snacks and overweight: findings from the Young Lives cohort study in Peru. Public HealthNutr. Jun 2018;21(9):1627–1633. doi:10.1017/S1368980018000320 | Intervention/Exposure
30 | Alwattar AY, Thyfault JP, Leidy HJ. The effect of breakfast type and frequency of consumption on glycemic response in overweight/obese late adolescent girls. Eur J Clin Nutr. Aug 2015;69(8):885–90. doi:10.1038/ejcn.2015.12 25711955 | Outcome
31 | Amosa T, Rush E, Plank L. Frequency of eating occasions reported by young New Zealand Polynesian and European women. Pac Health Dialog. Mar 2001;8(1):59–65.12017838 | Study design
32 | Andersson I, Lennernas M, Rossner S. Meal pattern and risk factor evaluation in one-year completers of a weight reduction program for obese men - the 'Gustaf' study. J Intern Med. Jan 2000;247(1):30–8. doi:10.1046/j.1365-2796.2000.00569.x 10672128 | Intervention/Exposure
33 | Andrade L, Zazpe I, Santiago S, Carlos S, Bes-Rastrollo M, Martinez-Gonzalez MA. Ten-Year Changesin Healthy Eating Attitudes in the SUN Cohort. J Am Coll Nutr. Jul 2017;36(5):319–329. doi:10.1080/07315724.2016.1278566 28506187 | Intervention/Exposure; Outcome
34 | Andrews L. Daily Breakfast Brings Weight Loss. Communicating Food for Health. 2017:7–8. | Study design
35 | Antoni R, Johnston KL, Collins AL, Robertson MD. Intermittent v. continuous energy restriction: differential effects on postprandial glucose and lipid metabolism following matched weight loss in overweight/obese participants. Br J Nutr. Mar 2018;119(5):507–516. doi:10.1017/S0007114517003890 29508693 | Intervention/Exposure
36 | Antoni R, Robertson TM, Robertson MD, Johnston JD. A pilot feasibility study exploring the effects of a moderate time-restricted feeding intervention on energy intake, adiposity and metabolic physiology in free-living human subjects. Article. Journal of Nutritional Science. Aug 30 2018;7doi:10.1017/jns.2018.13 | Intervention/Exposure
37 | Arabshahi S, Lahmann PH, Hughes MC, Williams GW, van der Pols JC. Dietary behaviours, weight loss attempts and change in waist circumference: 15-year longitudinal study in Australian adults. Asia Pac J Clin Nutr. 2017;26(4):657–664. doi:10.6133/apjcn.062016.04 28582816 | Intervention/Exposure
38 | Arciero PJ, Ormsbee MJ, Gentile CL, Nindl BC, Brestoff JR, Ruby M. Increased protein intake andmeal frequency reduces abdominal fat during energy balance and energy deficit. Obesity (Silver Spring). Jul 2013;21(7):1357–66. doi:10.1002/oby.20296 23703835 | Outcome; Duration
39 | Ardolino A. Snacking Series: Do Snacks Lead to Weight Gain? Food Insight. 2018:3–3. | Study design
40 | Arenaza L, Munoz-Hernandez V, Medrano M, Association of Breakfast Quality and Energy Density with Cardiometabolic Risk Factors in Overweight/Obese Children: Role of PhysicalActivity. Nutrients. Aug 10 2018;10(8)doi:10.3390/nu10081066 | Study design; Intervention/Exposure
41 | Asghari G, Yuzbashian E, Mirmiran P, Bahadoran Z, Azizi F. Prediction of metabolic syndrome by a high intake of energy-dense nutrient-poor snacks in Iranian children and adolescents. Pediatr Res. May 2016;79(5):697–704. doi:10.1038/pr.2015.270 26717004 | Intervention/Exposure
42 | Ashwell M, Hunty A. How does breakfast help manage bodyweight? Nutrition Bulletin. 2012;37(4):395–397. doi:10.1111/j.1467-3010.2012.01994.x | Study design
43 | Ask AS, Hernes S, Aarek I, Johannessen G, Haugen M. Changes in dietary pattern in 15 year old adolescents following a 4 month dietary intervention with school breakfast--a pilot study. Nutr J. Dec 7 2006;5:33. doi:10.1186/1475-2891-5-33 17150115 | Intervention/Exposure
44 | Azadbakht L, Haghighatdoost F, Feizi A, Esmaillzadeh A. Breakfast eating pattern and its association with dietary quality indices and anthropometric measurements in young women in Isfahan. Nutrition. Feb 2013;29(2):420–5. doi:10.1016/j.nut.2012.07.008 23312764 | Study design
45 | Bachman JL, Phelan S, Wing RR, Raynor HA. Eating frequency is higher in weight loss maintainers and normal-weight individuals than in overweight individuals. J Am Diet Assoc. Nov 2011;111(11):1730–4. doi:10.1016/j.jada.2011.08.006 22027056 | Study design
46 | Bailey BW, Sullivan DK, Kirk EP, Donnelly JE. Dietary predictors of visceral adiposity in overweight young adults. Br J Nutr. Jun 2010;103(12):1702–5. doi:10.1017/S0007114509993771 20100377 | Study design; Intervention/Exposure
47 | Balieiro LCT, Gontijo CA, Marot LP, Is chronotype associated with dietary intake and weight gain during pregnancy? A prospective and longitudinal study. Article. Nutrition. 2022;94doi:10.1016/j.nut.2021.111530 | Intervention/Exposure
48 | Ball K, Brown W, Crawford D. Who does not gain weight? Prevalence and predictors of weight maintenancein young women. Int J Obes Relat Metab Disord. Dec 2002;26(12):1570–8. doi:10.1038/sj.ijo.0802150 12461673 | Intervention/Exposure
49 | Bandin C, Scheer FA, Luque AJ, Meal timing affects glucose tolerance, substrate oxidation and circadian-related variables: A randomized, crossover trial. Int J Obes (Lond). May 2015;39(5):828–33. doi:10.1038/ijo.2014.182 25311083 | Intervention/Exposure; Comparator
50 | Bantle AE, Lau KJ, Wang Q, Time-restricted eating did not alter insulin sensitivity or beta-cell function in adults with obesity: A randomized pilot study. Obesity (Silver Spring). Feb 2023;31 Suppl 1(Suppl 1):108–115. doi:10.1002/oby.23620 36518093 | Intervention/Exposure
51 | Barba G, Troiano E, Russo P, Siani A, group APS. Total fat, fat distribution and blood pressure accordingto eating frequency in children living in southern Italy: the ARCA project. Int J Obes (Lond). Jul 2006;30(7):1166–9. doi:10.1038/sj.ijo.0803257 16462817 | Study design
52 | Baron KG, Reid KJ, Kern AS, Zee PC. Role of sleep timing in caloric intake and BMI. Obesity (Silver Spring). Jul 2011;19(7):1374–81. doi:10.1038/oby.2011.100 21527892 | Intervention/Exposure
53 | Barone Gibbs B, Kinzel LS, Pettee Gabriel K, Chang YF, Kuller LH. Short- and long-term eating habit modification predicts weight change in overweight, postmenopausal women: results from the WOMAN study. J Acad Nutr Diet. Sep 2012;112(9):1347–1355 e2. doi:10.1016/j.jand.2012.06.012 22939439 | Intervention/Exposure
54 | Basdeki ED, Argyris AA, Efthymiou O, Systematic Breakfast Consumption of Medium-Quantity and High-Quality Food Choices Is Associated with Better Vascular Health in Individuals with Cardiovascular Disease Risk Factors. Nutrients. Feb 18 2023;15(4)doi:10.3390/nu15041025 | Study design
55 | Basterra-Gortari FJ, Bes-Rastrollo M, Pardo-Fernandez M, Forga L, Martinez JA, Martinez-Gonzalez MA. Changes in weight and physical activity over two years in Spanish alumni. Med Sci Sports Exerc. Mar 2009;41(3):516–22. doi:10.1249/MSS.0b013e318188607c 19204600 | Intervention/Exposure
56 | Batista-Jorge GC, Barcala-Jorge AS, Oliveira Dias AF, Nutritional Status Associated to Skipping Breakfast in Brazilian Health Service Patients. Ann Nutr Metab. 2016;69(1):31–40. doi:10.1159/000447363 27434543 | Study design
57 | Bawaked RA, Gomez SF, Homs C, Association of eating behaviors, lifestyle, and maternal education with adherence to the Mediterranean diet in Spanish children. Appetite. Nov 1 2018;130:279–285. doi:10.1016/j.appet.2018.08.024 30130543 | Outcome
58 | Beaudry KM, Ludwa IA, Thomas AM, Ward WE, Falk B, Josse AR. First-year university is associatedwith greater body weight, body composition and adverse dietary changes in males than females. PLoS One. 2019;14(7):e0218554. doi:10.1371/journal.pone.0218554 31269047 | Intervention/Exposure; Outcome
59 | Beaulieu K, Casanova N, Oustric P, Matched Weight Loss Through Intermittent or ContinuousEnergy Restriction Does Not Lead To Compensatory Increases in Appetite and EatingBehavior in a Randomized Controlled Trial in Women with Overweight and Obesity. J Nutr. Mar 1 2020;150(3):623–633. doi:10.1093/jn/nxz296 31825067 | Intervention/Exposure
60 | Beaulieu K, Oustric P, Alkahtani S, Impact of Meal Timing and Chronotype on Food Rewardand Appetite Control in Young Adults. Nutrients. May 22 2020;12(5)doi:10.3390/nu12051506 | Intervention/Exposure; Outcome
61 | Befort CA, Stewart EE, Smith BK, Gibson CA, Sullivan DK, Donnelly JE. Weight maintenance, behaviors and barriers among previous participants of a university-based weight control program. Int J Obes (Lond). Mar 2008;32(3):519–26. doi:10.1038/sj.ijo.0803769 18059404 | Study design; Intervention/Exposure
62 | Belderson P, Harvey I, Kimbell R, O'Neill J, Russell J, Barker ME. Does breakfast-club attendance affect schoolchildren's nutrient intake? A study of dietary intake at three schools. Br JNutr. Dec 2003;90(6):1003–6. doi:10.1079/bjn20031011 14641958 | Study design; Intervention/Exposure
63 | Bellisle F. Impact of the daily meal pattern on energy balance. Scandinavian Journal of Nutrition. 2004;48(3):114–118. doi:10.1080/11026480410000454 | Study design
64 | Benton D, Jarvis M. The role of breakfast and a mid-morning snack on the ability of children to concentrateat school. Physiol Behav. Feb 28 2007;90(2–3):382–5. doi:10.1016/j.physbeh.2006.09.029 | Outcome
65 | Berendsen M, Boss M, Smits M, Pot GK. Chrono-Nutrition and Diet Quality in Adolescents with Delayed Sleep-Wake Phase Disorder. Nutrients. Feb 19 2020;12(2)doi:10.3390/nu12020539 | Intervention/Exposure
66 | Berentzen NE, Smit HA, van Rossem L, Screen time, adiposity and cardiometabolic markers: mediation by physical activity, not snacking, among 11-year-old children. Int J Obes (Lond). Oct 2014;38(10):1317–23. doi:10.1038/ijo.2014.110 24946910 | Intervention/Exposure
67 | Berge JM, MacLehose RF, Loth KA, Eisenberg ME, Fulkerson JA, Neumark-Sztainer D. Family meals. Associations with weight and eating behaviors among mothers and fathers. Appetite. Jun 2012;58(3):1128–35. doi:10.1016/j.appet.2012.03.008 22425759 | Intervention/Exposure
68 | Berge JM, Wall M, Hsueh TF, Fulkerson JA, Larson N, Neumark-Sztainer D. The protective role of family meals for youth obesity: 10-year longitudinal associations. J Pediatr. Feb 2015;166(2):296–301. doi:10.1016/j.jpeds.2014.08.030 | Intervention/Exposure
69 | Bernabe-Ortiz A, Mendoza-Quispe D, Jimenez MM, Ugaz ME, Rojas-Davila CE. Quantifying the childhood and adolescent overnutrition attributable to specific risk factors: The Young Lives Studyin Peru. Pediatr Obes. Apr 2023;18(4):e13002. doi:10.1111/ijpo.13002 36646441 | Intervention/Exposure
70 | Bes-Rastrollo M, Basterra-Gortari FJ, Sanchez-Villegas A, Marti A, Martinez JA, Martinez-Gonzalez MA. A prospective study of eating away-from-home meals and weight gain in a Mediterraneanpopulation: the SUN (Seguimiento Universidad de Navarra) cohort. Public Health Nutr. Sep 2010;13(9):1356–63. doi:10.1017/S1368980009992783 19954575 | Intervention/Exposure
71 | Bes-Rastrollo M, Sanchez-Villegas A, Gomez-Gracia E, Martinez JA, Pajares RM, Martinez-Gonzalez MA. Predictors of weight gain in a Mediterranean cohort: the Seguimiento Universidad de Navarra Study 1. Am J Clin Nutr. Feb 2006;83(2):362–70; quiz 394–5. doi:10.1093/ajcn/83.2.362 16469996 | Study design; Intervention/Exposure
72 | Beşoluk Ş. Association of dietary patterns with circadian preference, sleep and personality in highschool students. Article. Biological Rhythm Research. 2018;49(6):883–895. doi:10.1080/09291016.2018.1427601 | Study design; Outcome
73 | Beyerlein A, Fahrmeir L, Mansmann U, Toschke AM. Alternative regression models to assess increase in childhood BMI. BMC Med Res Methodol. Sep 8 2008;8:59. doi:10.1186/1471-2288-8-59 18778466 | Study design
74 | Bhutani S, vanDellen MR, Cooper JA. Longitudinal Weight Gain and Related Risk Behaviors duringthe COVID-19 Pandemic in Adults in the US. Nutrients. Feb 19 2021;13(2)doi:10.3390/nu13020671 | Study design; Outcome
75 | Bhutani S, Wells N, Finlayson G, Schoeller DA. Change in eating pattern as a contributor to energyintake and weight gain during the winter holiday period in obese adults. Int J Obes (Lond). Jul 2020;44(7):1586–1595. doi:10.1038/s41366-020-0562-2 32203107 | Intervention/Exposure
76 | Bin Naharudin MN, Yusof A, Shaw H, Stockton M, Clayton DJ, James LJ. Breakfast Omission ReducesSubsequent Resistance Exercise Performance. J Strength Cond Res. Jul 2019;33(7):1766–1772. doi:10.1519/JSC.0000000000003054 30707135 | Outcome
77 | Bjerre N, Holm L, Veje N, Quist JS, Faerch K, Hempler NF. What happens after a weight loss intervention? A qualitative study of drivers and challenges of maintaining time-restricted eating among people with overweight at high risk of type 2 diabetes. Appetite. Jul 1 2022;174:106034. doi:10.1016/j.appet.2022.106034 35378218 | Study design; Intervention/Exposure; Outcome
78 | Black MM, Papas MA, Bentley ME, Overweight adolescent African-American mothers gainweight in spite of intentions to lose weight. J Am Diet Assoc. Jan 2006;106(1):80–7. doi:10.1016/j.jada.2005.09.049 16390669 | Intervention/Exposure
79 | Bo L, Hutchison AT, Thompson CH, Effects of Intermittent Fasting or Calorie Restriction onMarkers of Lipid Metabolism in Human Skeletal Muscle. J Clin Endocrinol Metab. 2021;106(3):e1389–e1399. doi:10.1210/clinem/dgaa707 33031557 | Intervention/Exposure
80 | Bo S, De Carli L, Venco E, Impact of snacking pattern on overweight and obesity risk in a cohort of 11- to 13-year-old adolescents. J Pediatr Gastroenterol Nutr. Oct 2014;59(4):465–71. doi:10.1097/MPG.0000000000000453 24897170 | Study design
81 | Bo S, Fadda M, Castiglione A, Is the timing of caloric intake associated with variation in diet-induced thermogenesis and in the metabolic pattern? A randomized cross-over study. Journal Article; Clinical Trial Protocol. Int J Obes (Lond). 2015;39(12):1689‐1695. doi:10.1038/ijo.2015.138 26219416 | Intervention/Exposure; Comparator
82 | Bolze C, Gray-Donald K, Dugas EN, OĽoughlin J. Predictors of Weight Loss in Young Adults. Child Obes. Oct 2015;11(5):541–8. doi:10.1089/chi.2014.0160 26440384 | Intervention/Exposure
83 | Borg P, Fogelholm M, Kukkonen-Harjula K. Food selection and eating behaviour during weight maintenanceintervention and 2-y follow-up in obese men. Int J Obes Relat Metab Disord. Dec 2004;28(12):1548–54. doi:10.1038/sj.ijo.0802790 15543160 | Intervention/Exposure
84 | Boucher AB, Adesanya EA, Owei I, Dietary habits and leisure-time physical activity in relation to adiposity, dyslipidemia, and incident dysglycemia in the pathobiology of prediabetes ina biracial cohort study. Metabolism. Sep 2015;64(9):1060–7. doi:10.1016/j.metabol.2015.05.015 26116207 | Intervention/Exposure
85 | Boynton A, Neuhouser ML, Sorensen B, McTiernan A, Ulrich CM. Predictors of diet quality amongoverweight and obese postmenopausal women. J Am Diet Assoc. Jan 2008;108(1):125–30. doi:10.1016/j.jada.2007.10.037 18155998 | Study design; Intervention/Exposure
86 | Brady AJ, Langton HM, Mulligan M, Egan B. Effects of 8 wk of 16:8 Time-restricted Eating in MaleMiddle- and Long-Distance Runners. Med Sci Sports Exerc. Mar 1 2021;53(3):633–642. doi:10.1249/MSS.0000000000002488 32796255 | Intervention/Exposure
87 | Brikou D, Zannidi D, Karfopoulou E, Anastasiou CA, Yannakoulia M. Breakfast consumption and weight-loss maintenance: results from the MedWeight study. Br J Nutr. Jun 2016;115(12):2246–51. doi:10.1017/S0007114516001550 27185413 | Study design
88 | Bruening M, Larson N, Story M, Neumark-Sztainer D, Hannan P. Predictors of adolescent breakfast consumption: longitudinal findings from Project EAT. J Nutr Educ Behav. Sep-Oct 2011;43(5):390–5. doi:10.1016/j.jneb.2011.02.016 21906551 | Intervention/Exposure; Outcome
89 | Burgess-Champoux TL, Larson N, Neumark-Sztainer D, Hannan PJ, Story M. Are family meal patterns associated with overall diet quality during the transition from early to middle adolescence? J Nutr Educ Behav. Mar-Apr 2009;41(2):79–86. doi:10.1016/j.jneb.2008.03.113 19304252 | Intervention/Exposure; Outcome
90 | Buscemi J, Berlin KS, Rybak TM, Health Behavior and Weight Changes Among Ethnic andRacial Minority Preschoolers and Their Parents: Associations Across 1 Year. J Pediatr Psychol. Aug 2016;41(7):777–85. doi:10.1093/jpepsy/jsv165 26717958 | Intervention/Exposure
91 | Buyken AE, Trauner K, Gunther AL, Kroke A, Remer T. Breakfast glycemic index affects subsequentdaily energy intake in free-living healthy children. Am J Clin Nutr. Oct 2007;86(4):980–7. doi:10.1093/ajcn/86.4.980 17921374 | Intervention/Exposure
92 | Cachelin FM, Thomas C, Vela A, Gil-Rivas V. Associations between meal patterns, binge eating, and weight for Latinas. Int J Eat Disord. Jan 2017;50(1):32–39. doi:10.1002/eat.22580 27436488 | Study design
93 | Cahill LE. About time: eating timing is a complex risk factor for obesity. Am J Clin Nutr. Jan 4 2021;113(1):5–6. doi:10.1093/ajcn/nqaa329 33300034 | Study design
94 | Calamaro CJ, Park S, Mason TB, Shortened sleep duration does not predict obesity in adolescents. J Sleep Res. Dec 2010;19(4):559–66. doi:10.1111/j.1365-2869.2010.00840.x 20545836 | Study design; Intervention/Exposure
95 | Calleja Fernández A, Muñoz Weigand C, Ballesteros Pomar MD, Modificación de los hábitos alimentarios del almuerzo en una población escolar [Changes on dietary habits of the late-breakfast in a school population]. Nutrición Hospitalaria. 2011;26(3):560–565. doi:10.1590/S0212-16112011000300019 21892575 | Intervention/Exposure; Language
96 | Cameron JD, Cyr MJ, Doucet E. Increased meal frequency does not promote greater weight lossin subjects who were prescribed an 8-week equi-energetic energy-restricted diet. Br J Nutr. Apr 2010;103(8):1098–101. doi:10.1017/S0007114509992984 19943985 | Duration
97 | Capaldi ED, Owens JQ, Privitera GJ. Isocaloric meal and snack foods differentially affect eating behavior. Appetite. Mar 2006;46(2):117–23. doi:10.1016/j.appet.2005.10.008 16442668 | Comparator
98 | Carels RA, Young KM, Coit C, Clayton AM, Spencer A, Wagner M. Skipping meals and alcohol consumption. The regulation of energy intake and expenditure among weight loss participants. Appetite. Nov 2008;51(3):538–45. doi:10.1016/j.appet.2008.04.006 18511146 | Study design
99 | Carew AS, Mekary RA, Kirkland S, Prospective Study of Skipping Meals to Lose Weight as a Predictor of Incident Type 2 Diabetes With Potential Modification by Cardiometabolic Risk Factors: The Canadian 1995 Nova Scotia Health Survey. Can J Diabetes. Jun 2021;45(4):306–312. doi:10.1016/j.jcjd.2020.09.009 33218923 | Outcome
100 | Carlson JA, Crespo NC, Sallis JF, Patterson RE, Elder JP. Dietary-related and physical activity-related predictors of obesity in children: a 2-year prospective study. Child Obes. Apr 2012;8(2):110–5. doi:10.1089/chi.2011.0071 22799510 | Intervention/Exposure
101 | Carlson O, Martin B, Stote KS, Impact of reduced meal frequency without caloric restriction on glucose regulation in healthy, normal-weight middle-aged men and women. Metabolism. Dec 2007;56(12):1729–34. doi:10.1016/j.metabol.2007.07.018 17998028 | Comparator; Outcome; Duration
102 | Carnell S, Papantoni A, Grillot CL, Time of day differences in appetite and gut hormone responsesto meal and stress challenges in adults with normal-weight and obesity. Physiol Behav. Oct 1 2022;254:113890. doi:10.1016/j.physbeh.2022.113890 35750246 | Intervention/Exposure
103 | Carriere C, Langevin C, Lamireau T, Maurice S, Thibault H. Dietary behaviors as associated factorsfor overweight and obesity in a sample of adolescents from Aquitaine, France. J Physiol Biochem. Mar 2013;69(1):111–8. doi:10.1007/s13105-012-0194-7 22773296 | Study design
104 | Chang Y, Gable S. Predicting weight status stability and change from fifth grade to eighth grade: the significant role of adolescents' social-emotional well-being. J Adolesc Health. Apr 2013;52(4):448–55. doi:10.1016/j.jadohealth.2012.09.005 23298991 | Intervention/Exposure
105 | Chapelot D, Marmonier C, Aubert R, Consequence of omitting or adding a meal in man on body composition, food intake, and metabolism. Obesity (Silver Spring). Feb 2006;14(2):215–27. doi:10.1038/oby.2006.28 16571846 | Study design
106 | Chapelot D, Marmonier C, Aubert R, Gausseres N, Louis-Sylvestre J. A role for glucose and insulin preprandial profiles to differentiate meals and snacks. Physiol Behav. Feb 2004;80(5):721–31. doi:10.1016/j.physbeh.2003.12.006 14984807 | Outcome
107 | Chen C, ValizadehAslani T, Rosen GL, Anderson LM, Jungquist CR. Healthcare Shift Workers' Temporal Habits for Eating, Sleeping, and Light Exposure: A Multi-Instrument Pilot Study. Article. J Circadian Rhythms. Oct 21 2020;18(1):6. doi:10.5334/jcr.199 33133210 | Intervention/Exposure
108 | Chen CY, Hsiao YC. Dual trajectories of breakfast eating and fruit and vegetable intake over a 5-year follow-up period among economically disadvantaged children: Gender differences. Appetite. Feb 1 2018;121:41–49. doi:10.1016/j.appet.2017.10.027 29079477 | Outcome
109 | Chen JL, Wall D, Kennedy C, Unnithan V, Yeh CH. Predictors of increased body mass index in Chinese children. Prog Cardiovasc Nurs. Summer 2007;22(3):138–44. doi:10.1111/j.0889-7204.2007.05668.x 17786089 | Intervention/Exposure
110 | Cheng ER, Carroll AE. Offering Breakfast in the Classroom and Children's Weight Outcomes. JAMA Pediatr. Apr 1 2019;173(4):317–318. doi:10.1001/jamapediatrics.2018.5539 30801619 | Study design
111 | Cheng TS, Loy SL, Toh JY, Predominantly nighttime feeding and weight outcomes in infants. Am J Clin Nutr. Aug 2016;104(2):380–8. doi:10.3945/ajcn.116.130765 27385614 | Population Life Stage; Intervention/Exposure
112 | Chin SO, Keum C, Woo J, Successful weight reduction and maintenance by using a smartphoneapplication in those with overweight and obesity. Sci Rep. Nov 7 2016;6:34563. doi:10.1038/srep34563 27819345 | Intervention/Exposure
113 | Chiu CH, Chen CH, Wu MH, 5 days of time-restricted feeding increases fat oxidation rate butnot affect postprandial lipemia: a crossover trial. Sci Rep. Jun 3 2022;12(1):9295. doi:10.1038/s41598-022-13387-8 35661801 | Intervention/Exposure
114 | Cho S, Alberding J, Sadler B, Johnson KJ, Clark C. Worksite weight loss program with meal and snack replacement system: Twelve-week results. Journal article. Am J Clin Nutr. Feb 2002;75(2):383s-383s. doi:10.1093/ajcn/75.2.339S | Intervention/Exposure; Publication status
115 | Chow LS, Manoogian ENC, Alvear A, Time-Restricted Eating Effects on Body Composition and Metabolic Measures in Humans who are Overweight: A Feasibility Study. Journal article. Obesity (Silver Spring). May 2020;28(5):860–869. doi:10.1002/oby.22756 | Intervention/Exposure
116 | Christensen CB, Mikkelsen BE, Toft U. The effect of introducing a free breakfast club on eating habitsamong students at vocational schools. BMC Public Health. Apr 3 2019;19(1):369. doi:10.1186/s12889-019-6701-9 30943941 | Intervention/Exposure; Outcome
117 | Christoph MJ, Larson NI, Winkler MR, Wall MM, Neumark-Sztainer D. Longitudinal trajectories andprevalence of meeting dietary guidelines during the transition from adolescence to young adulthood. Am J Clin Nutr. Mar 1 2019;109(3):656–664. doi:10.1093/ajcn/nqy333 30831584 | Intervention/Exposure
118 | Chui JM, Lacy KE, Zheng MJ, Leech RM, McNaughton SA, Spence AC. Frequency and distribution of dietary energy, vegetable, fruit and discretionary food intakes in 18-month-old Australianchildren. Article in Press. Br J Nutr. Aug 14 2023;130(3):513–524. doi:10.1017/S0007114522003324 36268727 | Study design; Intervention/Exposure
119 | Chung S, Popkin BM, Domino ME, Stearns SC. Effect of retirement on eating out and weight change: an analysis of gender differences. Obesity (Silver Spring). Apr 2007;15(4):1053–60. doi:10.1038/oby.2007.538 17426342 | Intervention/Exposure
120 | Cienfuegos S, Gabel K, Kalam F, Ezpeleta M, Lin S, Varady KA. Changes in body weight and metabolic risk during time restricted feeding in premenopausal versus postmenopausal women. Exp Gerontol. Oct 15 2021;154:111545. doi:10.1016/j.exger.2021.111545 34478825 | Intervention/Exposure
121 | Cienfuegos S, Gabel K, Kalam F, The effect of 4-h versus 6-h time restricted feeding on sleepquality, duration, insomnia severity and obstructive sleep apnea in adults with obesity. Nutr Health. Mar 2022;28(1):5–11. doi:10.1177/02601060211002347 33759620 | Intervention/Exposure
122 | Cienfuegos S, Gabel K, Kalam F, Effects of 4- and 6-h Time-Restricted Feeding on Weight and Cardiometabolic Health: A Randomized Controlled Trial in Adults with Obesity. Cell Metab. Sep 1 2020;32(3):366–378 e3. doi:10.1016/j.cmet.2020.06.018 32673591 | Intervention/Exposure
123 | Cipolla C, Curatola A, Ferretti S, Eating habits and lifestyle in children with obesity during theCOVID19 lockdown: a survey in an Italian center. Acta Biomed. May 12 2021;92(2):e2021196. doi:10.23750/abm.v92i2.10912 33988154 | Study design
124 | Clark DO, Keith NR, Ofner S, Environments and situations as correlates of eating and drinkingamong women living with obesity and urban poverty. Obes Sci Pract. Apr 2022;8(2):153–163. doi:10.1002/osp4.557 35388340 | Study design
125 | Clayton DJ, Stensel DJ, James LJ. Effect of breakfast omission on subjective appetite, metabolism, acylated ghrelin and GLP-17–36 during rest and exercise. Nutrition. Feb 2016;32(2):179–85. doi:10.1016/j.nut.2015.06.013 26421384 | Outcome
126 | Cohen DA, Ghosh-Dastidar B, Conway TL, Energy balance in adolescent girls: the trial of activity for adolescent girls cohort. Obesity (Silver Spring). Mar 2014;22(3):772–80. doi:10.1002/oby.20536 23804512 | Intervention/Exposure
127 | Colles SL, Dixon JB, O'Brien PE. Night eating syndrome and nocturnal snacking: association with obesity, binge eating and psychological distress. Int J Obes (Lond). Nov 2007;31(11):1722–30. doi:10.1038/sj.ijo.0803664 17579633 | Study design; Intervention/Exposure
128 | Collings PJ, Kelly B, West J, Wright J. Associations of TV Viewing Duration, Meals and Snacks EatenWhen Watching TV, and a TV in the Bedroom with Child Adiposity. Obesity (Silver Spring). Oct 2018;26(10):1619–1628. doi:10.1002/oby.22288 30269425 | Study design; Intervention/Exposure
129 | Corbalan-Tutau MD, Madrid JA, Garaulet M. Timing and duration of sleep and meals in obese andnormal weight women. Association with increase blood pressure. Appetite. Aug 2012;59(1):9–16. doi:10.1016/j.appet.2012.03.015 22450522 | Intervention/Exposure
130 | Correia JM, Santos I, Pezarat-Correia P, Minderico C, Schoenfeld BJ, Mendonca GV. Effects of Time-Restricted Feeding on Supramaximal Exercise Performance and Body Composition: A Randomized and Counterbalanced Crossover Study in Healthy Men. Int J Environ Res Public Health. Jul 6 2021;18(14)doi:10.3390/ijerph18147227 | Intervention/Exposure
131 | Correia JM, Santos PDG, Pezarat-Correia P, Minderico CS, Infante J, Mendonca GV. Effect of Time-Restricted Eating and Resistance Training on High-Speed Strength and Body Composition. Nutrients. Jan 6 2023;15(2)doi:10.3390/nu15020285 | Intervention/Exposure
132 | Crepinsek MK, Singh A, Bernstein LS, McLaughlin JE. Dietary effects of universal-free school breakfast: findings from the evaluation of the school breakfast program pilot project. J Am Diet Assoc. Nov 2006;106(11):1796–803. doi:10.1016/j.jada.2006.08.013 17081831 | Intervention/Exposure
133 | Crimarco A, Turner-McGrievy GM, Wirth MD. The effects of meal-timing on self-rated hunger and dietary inflammatory potential among a sample of college students. J Am Coll Health. May-Jun 2019;67(4):328–337. doi:10.1080/07448481.2018.1481074 29979952 | Intervention/Exposure; Comparator
134 | Crose A, Alvear A, Singroy S, Time-Restricted Eating Improves Quality of Life Measures in Overweight Humans. Nutrients. Apr 23 2021;13(5)doi:10.3390/nu13051430 | Intervention/Exposure
135 | Culnan E, Reid KJ, Zee PC, Crowley SJ, Baron KG. Meal timing relative to DLMO: Associations with BMI and body fat. Sleep Health. Jun 2021;7(3):339–344. doi:10.1016/j.sleh.2021.01.001 33610479 | Intervention/Exposure
136 | Currenti W, Buscemi S, Cincione RI, Time-Restricted Feeding and Metabolic Outcomes in a Cohort of Italian Adults. Nutrients. May 13 2021;13(5)doi:10.3390/nu13051651 | Intervention/Exposure
137 | Cutler GJ, Flood A, Hannan P, Neumark-Sztainer D. Multiple sociodemographic and socioenvironmentalcharacteristics are correlated with major patterns of dietary intake in adolescents. J Am Diet Assoc. Feb 2011;111(2):230–40. doi:10.1016/j.jada.2010.10.052 21272697 | Intervention/Exposure; Outcome
138 | Daly P. Obese adolescent females and actual behavioral responses to a mindful eating intervention. Dissertation. The University of Arizona; 2013. https://repository.arizona.edu/handle/10150/311457 | Study design; Publication status
139 | Daniel MM, Liboredo JC, Anastacio LR, Incidence and Associated Factors of Weight Gain During the Covid-19 Pandemic. Front Nutr. 2022;9:818632. doi:10.3389/fnut.2022.818632 35284434 | Study design
140 | Daniels SR. Breakfast is important. Article. J Pediatr. 2012;161(5):A1. doi:10.1016/j.jpeds.2012.09.029 | Study design
141 | Dashti HS, Gomez-Abellan P, Qian J, Late eating is associated with cardiometabolic risk traits, obesogenic behaviors, and impaired weight loss. Am J Clin Nutr. Jan 4 2021;113(1):154–161. doi:10.1093/ajcn/nqaa264 33022698 | Study design
142 | Dashti HS, Merino J, Lane JM, Genome-wide association study of breakfast skipping links clockregulation with food timing. Am J Clin Nutr. Aug 1 2019;110(2):473–484. doi:10.1093/ajcn/nqz076 31190057 | Intervention/Exposure; Comparator
143 | Davis J, Shriver L, Taylor C, Ramsay S. Frequency of Eating Occasions and Relation to Weight Statusin Children 2–5 Years of Age. J Acad Nutr Diet. 2016;116:A52–A52. doi:10.1016/j.jand.2016.06.176 | Publication status
144 | de Castro JM. The time of day of food intake influences overall intake in humans. J Nutr. Jan 2004;134(1):104–11. doi:10.1093/jn/134.1.104 14704301 | Intervention/Exposure
145 | de Oliveira Maranhao Pureza IR, da Silva Junior AE, Silva Praxedes DR, Effects of time-restricted feeding on body weight, body composition and vital signs in low-income women with obesity: A 12-month randomized clinical trial. Clin Nutr. Mar 2021;40(3):759–766. doi:10.1016/j.clnu.2020.06.036 32713721 | Intervention/Exposure
146 | de Oliveira Santos R, Fisberg RM, Marchioni DM, Troncoso Baltar V. Dietary patterns for meals of Brazilian adults. Br J Nutr. Sep 14 2015;114(5):822–8. doi:10.1017/S0007114515002445 26220554 | Study design; Intervention/Exposure; Outcome
147 | de Silva-Sanigorski AM, Bell AC, Kremer P, Reducing obesity in early childhood: results from Romp & Chomp, an Australian community-wide intervention program. Am J Clin Nutr. Apr 2010;91(4):831–40. doi:10.3945/ajcn.2009.28826 20147472 | Intervention/Exposure
148 | Deforche B, Van Dyck D, Deliens T, De Bourdeaudhuij I. Changes in weight, physical activity, sedentary behaviour and dietary intake during the transition to higher education: a prospective study. Int J Behav Nutr Phys Act. Feb 15 2015;12:16. doi:10.1186/s12966-015-0173-9 25881147 | Intervention/Exposure
149 | Deliens T, Clarys P, Van Hecke L, De Bourdeaudhuij I, Deforche B. Changes in weight and body composition during the first semester at university. A prospective explanatory study. Appetite. Jun 2013;65:111–6. doi:10.1016/j.appet.2013.01.024 23402710 | Intervention/Exposure
150 | Deschasaux-Tanguy M, Druesne-Pecollo N, Esseddik Y, Diet and physical activity during the coronavirus disease 2019 (COVID-19) lockdown (March-May 2020): results from the FrenchNutriNet-Sante cohort study. Am J Clin Nutr. Apr 6 2021;113(4):924–938. doi:10.1093/ajcn/nqaa336 33675635 | Intervention/Exposure
151 | Deying L, Yan H, Chensihan H, Calorie Restriction with or without Time-Restricted Eating in Weight Loss. N Engl J Med. 2022;386(16):1495–1504. doi:10.1056/NEJMoa2114833 35443107 | Intervention/Exposure
152 | Dicken SJ, Mitchell JJ, Newberry Le Vay J, Impact of the COVID-19 Pandemic on Diet Behaviour Among UK Adults: A Longitudinal Analysis of the HEBECO Study. Front Nutr. 2021;8:788043. doi:10.3389/fnut.2021.788043 35096934 | Intervention/Exposure; Outcome
153 | Domaszewski P, Konieczny M, Dybek T, Comparison of the effects of six-week time-restricted eating on weight loss, body composition, and visceral fat in overweight older men and women. Exp Gerontol. Apr 2023;174:112116. doi:10.1016/j.exger.2023.112116 36739795 | Intervention/Exposure
154 | Domaszewski P, Konieczny M, Pakosz P, Effect of a six-week times restricted eating interventionon the body composition in early elderly men with overweight. Sci Rep. Jun 14 2022;12(1):9816. doi:10.1038/s41598-022-13904-9 35701451 | Intervention/Exposure
155 | Dong F, Howard AG, Herring AH, Longitudinal associations of away-from-home eating, snacking, screen time, and physical activity behaviors with cardiometabolic risk factors among Chinesechildren and their parents. Am J Clin Nutr. Jul 2017;106(1):168–178. doi:10.3945/ajcn.116.146217 28539376 | Intervention/Exposure
156 | Dougkas A, Minihane AM, Givens DI, Reynolds CK, Yaqoob P. Differential effects of dairy snacks on appetite, but not overall energy intake. Br J Nutr. Dec 28 2012;108(12):2274–85. doi:10.1017/S0007114512000323 22380537 | Intervention/Exposure
157 | Douglas SM, Byers AW, Leidy HJ. Habitual Breakfast Patterns Do Not Influence Appetite and Satiety Responses in Normal vs. High-Protein Breakfasts in Overweight Adolescent Girls. Nutrients. May 29 2019;11(6)doi:10.3390/nu11061223 | Intervention/Exposure
158 | Duan D, Pilla SJ, Michalski K, Laferrere B, Clark JM, Maruthur NM. Eating breakfast is associated with weight loss during an intensive lifestyle intervention for overweight/obesity. Obesity (Silver Spring). Feb 2022;30(2):378–388. doi:10.1002/oby.23340 35048528 | Health status
159 | Dubois L, Bedard B, Goulet D, Prud'homme D, Tremblay RE, Boivin M. Eating behaviors, dietary patterns and weight status in emerging adulthood and longitudinal associations with eating behaviors in early childhood. Int J Behav Nutr Phys Act. Nov 16 2022;19(1):139. doi:10.1186/s12966-022-01376-z 36384744 | Intervention/Exposure
160 | Dubois L, Farmer A, Girard M, Peterson K. Social factors and television use during meals and snacksis associated with higher BMI among pre-school children. Public Health Nutr. Dec 2008;11(12):1267–79. doi:10.1017/S1368980008002887 18547454 | Intervention/Exposure
161 | Dubois L, Girard M, Kent MP. Breakfast eating and overweight in a pre-school population: Is there a link? Article. Public Health Nutr. 2006;9(4):436–442. doi:10.1079/phn2005867 16870015 | Study design
162 | Ducrot P, Mejean C, Bellisle F, Alles B, Hercberg S, Peneau S. Adherence to the French Eating Modelis inversely associated with overweight and obesity: results from a large sample of French adults. Br J Nutr. Jul 2018;120(2):231–239. doi:10.1017/S0007114518000909 29781419 | Study design
163 | Duffey KJ, Gordon-Larsen P, Jacobs DR Jr., Williams OD, Popkin BM. Differential associations offast food and restaurant food consumption with 3-y change in body mass index: the CoronaryArtery Risk Development in Young Adults Study. Am J Clin Nutr. Jan 2007;85(1):201–8. doi:10.1093/ajcn/85.1.201 17209197 | Intervention/Exposure
164 | Durao C, Severo M, Oliveira A, Lopes C. Sex-Heterogeneity on the Association between DietaryPatterns at 4 Years of Age with Adiposity and Cardiometabolic Risk Factors at 10 Years of Age. Nutrients. Jan 26 2022;14(3)doi:10.3390/nu14030540 | Intervention/Exposure
165 | Durao C, Severo M, Oliveira A, Association between dietary patterns and adiposity from 4 to 7 years of age. Public Health Nutr. Aug 2017;20(11):1973–1982. doi:10.1017/S1368980017000854 28534458 | Intervention/Exposure
166 | Duval K, Strychar I, Cyr MJ, Prud'homme D, Rabasa-Lhoret R, Doucet E. Physical activity is a confounding factor of the relation between eating frequency and body composition. Am J Clin Nutr. Nov 2008;88(5):1200–5. doi:10.3945/ajcn.2008.26220 18996853 | Study design
167 | Eagle TF, Gurm R, Goldberg CS, Health status and behavior among middle-school childrenin a midwest community: what are the underpinnings of childhood obesity? Am Heart J. Dec 2010;160(6):1185–9. doi:10.1016/j.ahj.2010.09.019 21146676 | Study design; Intervention/Exposure
168 | Elimam A, Marcus C. Meal timing, fasting and glucocorticoids interplay in serum leptin concentrationsand diurnal profile. Eur J Endocrinol. Aug 2002;147(2):181–8. doi:10.1530/eje.0.1470181 12153738 | Intervention/Exposure; Outcome
169 | Elinder LS, Heinemans N, Zeebari Z, Patterson E. Longitudinal changes in health behaviours and body weight among Swedish school children--associations with age, gender and parental education--the SCIP school cohort. BMC Public Health. Jun 23 2014;14:640. doi:10.1186/1471-2458-14-640 24958251 | Outcome
170 | Elseifi OS, Abdelrahman DM, Mortada EM. Effect of a nutritional education intervention on breakfastconsumption among preparatory school students in Egypt. Int J Public Health. Jul 2020;65(6):893–903. doi:10.1007/s00038-020-01439-7 32725393 | Study design; Intervention/Exposure
171 | Embling R, Price MJ, Lee MD, Jones A, Wilkinson LL. Associations between dietary variety, portion size and body weight: prospective evidence from UK Biobank participants. Article in Press. British Journal of Nutrition. Oct 14 2023;130(7):1267–1277. doi:10.1017/S0007114523000156 36645103 | Intervention/Exposure
172 | Englund-Ogge L, Birgisdottir BE, Sengpiel V, Meal frequency patterns and glycemic propertiesof maternal diet in relation to preterm delivery: Results from a large prospective cohort study. PLoS One. 2017;12(3):e0172896. doi:10.1371/journal.pone.0172896 28249018 | Outcome
173 | Eom H, Lee D, Cho Y, Moon J. The association between meal regularity and weight loss amongwomen in commercial weight loss programs. Nutr Res Pract. Apr 2022;16(2):205–216. doi:10.4162/nrp.2022.16.2.205 35392532 | Intervention/Exposure
174 | Epel E, Jimenez S, Brownell K, Stroud L, Stoney C, Niaura R. Are stress eaters at risk for the metabolic syndrome? Ann N Y Acad Sci. Dec 2004;1032:208–10. doi:10.1196/annals.1314.022 15677412 | Intervention/Exposure
175 | Erdem NZ, Bayraktaroglu E, Samanci RA, Gecgil-Demir E, Tarakci NG, Mert-Biberoglu F. The effectof intermittent fasting diets on body weight and composition. Journal article. Clin Nutr ESPEN. Oct 2022;51:207–214. doi:10.1016/j.clnesp.2022.08.030 36184206 | Intervention/Exposure
176 | Estabrooks PA, Shoup JA, Gattshall M, Dandamudi P, Shetterly S, Xu S. Automated telephone counseling for parents of overweight children: a randomized controlled trial. Am J Prev Med. Jan 2009;36(1):35–42. doi:10.1016/j.amepre.2008.09.024 19095163 | Intervention/Exposure
177 | Fagundes GBP, Tibaes JRB, Silva ML, Metabolic and behavioral effects of time-restricted eating in women with overweight or obesity: Preliminary findings from a randomized study. Journal article. Nutrition. Mar 2023;107:111909. doi:10.1016/j.nut.2022.111909 36571891 | Intervention/Exposure
178 | Fairclough SJ, Hackett AF, Davies IG, Promoting healthy weight in primary school children through physical activity and nutrition education: a pragmatic evaluation of the CHANGE! randomised intervention study. BMC Public Health. Jul 2 2013;13:626. doi:10.1186/1471-2458-13-626 23819701 | Intervention/Exposure
179 | Fanelli S, Walls C, Taylor C. Skipping breakfast is associated with nutrient gaps and poorer diet quality among adults in the United States. Proceedings of the Nutrition Society. 2021;80(Oce1):1–1. doi:10.1017/S0029665121000495 32441238 | Study design; Publication status
180 | Farajian P, Risvas G, Karasouli K, Very high childhood obesity prevalence and low adherence rates to the Mediterranean diet in Greek children: the GRECO study. Atherosclerosis. Aug 2011;217(2):525–30. doi:10.1016/j.atherosclerosis.2011.04.003 21561621 | Study design
181 | Farshchi HR, Taylor MA, Macdonald IA. Regular meal frequency creates more appropriate insulinsensitivity and lipid profiles compared with irregular meal frequency in healthy lean women. Eur J Clin Nutr. Jul 2004;58(7):1071–7. doi:10.1038/sj.ejcn.1601935 15220950 | Comparator
182 | Farshchi HR, Taylor MA, Macdonald IA. Beneficial metabolic effects of regular meal frequency on dietary thermogenesis, insulin sensitivity, and fasting lipid profiles in healthy obese women. Am J Clin Nutr. Jan 2005;81(1):16–24. doi:10.1093/ajcn/81.1.16 15640455 | Comparator
183 | Fearnbach N, Staiano AE, Johannsen NM, Predictors of Post-Exercise Energy Intake in AdolescentsRanging in Weight Status from Overweight to Severe Obesity. Nutrients. Jan 5 2022;14(1)doi:10.3390/nu14010223 | Intervention/Exposure
184 | Feeley AB, Musenge E, Pettifor JM, Norris SA. Investigation into longitudinal dietary behaviours and household socio-economic indicators and their association with BMI Z-score and fat mass in South African adolescents: the Birth to Twenty (Bt20) cohort. Public Health Nutr. Apr 2013;16(4):693–703. doi:10.1017/S1368980012003308 22801035 | Country
185 | Ferrocino I, Pellegrini M, D'Eusebio C, The Effects of Time-Restricted Eating on Metabolism and Gut Microbiota: A Real-Life Study. Nutrients. Jun 21 2022;14(13)doi:10.3390/nu14132569 | Intervention/Exposure
186 | Field AE, Austin SB, Gillman MW, Rosner B, Rockett HR, Colditz GA. Snack food intake does not predict weight change among children and adolescents. Int J Obes Relat Metab Disord. Oct 2004;28(10):1210–6. doi:10.1038/sj.ijo.0802762 15314623 | Intervention/Exposure
187 | Field AE, Austin SB, Taylor CB, Relation between dieting and weight change among preadolescentsand adolescents. Pediatrics. Oct 2003;112(4):900–6. doi:10.1542/peds.112.4.900 | Intervention/Exposure
188 | Fisher JO, Polonsky H, Bauer K, Increasing Breakfast Consumption and Decreasing ChildhoodObesity in Low-Income, Ethnically Diverse Youth. J Nutr Educ Behav. 2015;47:S99– S99. doi:10.1016/j.jneb.2015.04.266 | Study design; Publication status
189 | Flanagan A, Lowson E, Griffin BA, Skene DJ. Effects of Maternal Nightshift Work on Evening EnergyIntake, Diet Quality and Meal Timing in the Family: An Observational Study. Nurs Rep. Oct 22 2021;11(4):823–831. doi:10.3390/nursrep11040077 34968271 | Intervention/Exposure
190 | Fleischer JG, Das SK, Bhapkar M, Manoogian ENC, Panda S. Associations between the timing of eating and weight-loss in calorically restricted healthy adults: Findings from the CALERIE study. Exp Gerontol. Aug 2022;165:111837. doi:10.1016/j.exger.2022.111837 35598698 | Intervention/Exposure
191 | Flores G, Lin H. Factors predicting severe childhood obesity in kindergarteners. Int J Obes (Lond). Jan 2013;37(1):31–9. doi:10.1038/ijo.2012.168 23147114 | Intervention/Exposure
192 | Fogel A, Goh AT, Fries LR, A description of an 'obesogenic' eating style that promotes higher energy intake and is associated with greater adiposity in 4.5year-old children: Results from the GUSTO cohort. Physiol Behav. Jul 1 2017;176:107–116. doi:10.1016/j.physbeh.2017.02.013 28213204 | Intervention/Exposure
193 | Fogteloo AJ, Pijl H, Roelfsema F, Frolich M, Meinders AE. Impact of meal timing and frequency on the twenty-four-hour leptin rhythm. Horm Res. 2004;62(2):71–8. doi:10.1159/000079326 15218336 | Outcome
194 | Ford MC, Gordon NP, Howell A, Obesity Severity, Dietary Behaviors, and Lifestyle Risks Varyby Race/Ethnicity and Age in a Northern California Cohort of Children with Obesity. J Obes. 2016;2016:4287976. doi:10.1155/2016/4287976 26885385 | Study design
195 | Ford S. Skipping breakfast 'does not lead to overeating later in day'. Nursing Times. 2017:168– 168. | Study design
196 | Forde CG, Fogel A, McCrickerd K. Children's Eating Behaviors and Energy Intake: Overlapping Influences and Opportunities for Intervention. Nestle Nutr Inst Workshop Ser. 2019;91:55–67. doi:10.1159/000493695 30865959 | Study design; Intervention/Exposure
197 | Forkert ECO, Moraes ACF, Carvalho HB, Skipping breakfast is associated with adiposity markersespecially when sleep time is adequate in adolescents. Sci Rep. Apr 23 2019;9(1):6380. doi:10.1038/s41598-019-42859-7 31011180 | Study design
198 | Fortes Lde S, Almeida Sde S, Cipriani FM, Ferreira ME. Inappropriate eating behavior: a longitudinalstudy with female adolescents. Rev Paul Pediatr. Mar 2014;32(1):85–91. doi:10.1590/s0103-05822014000100014 24676195 | Intervention/Exposure
199 | Franca EB, Mendes KG, Theodoro H, Olinto MTA, Canuto R. Association of dietary patterns, number of daily meals and anthropometric measures in women in age of menopause. Article. Arch Endocrinol Metab. Nov 24 2021;65(6):778–786. doi:10.20945/2359-3997000000414 34762784 | Study design
200 | Francis LA, Rollins BY, Bryce CI, Granger DA. Biobehavioral Dysregulation and its Association with Obesity and Severe Obesity Trajectories from 2 to 15 Years of Age: A Longitudinal Study. Obesity (Silver Spring). Apr 2020;28(4):830–839. doi:10.1002/oby.22762 32202074 | Intervention/Exposure
201 | Freak-Poli RL, Wolfe R, Walls H, Backholer K, Peeters A. Participant characteristics associated with greater reductions in waist circumference during a four-month, pedometer-based, workplace health program. BMC Public Health. Oct 25 2011;11:824. doi:10.1186/1471-2458-11-824 22024045 | Study design; Intervention/Exposure
202 | French SA, Mitchell NR, Wolfson J, Portion size effects on weight gain in a free living setting. Obesity (Silver Spring). Jun 2014;22(6):1400–5. doi:10.1002/oby.20720 24510841 | Intervention/Exposure
203 | Fuglestad PT, Jeffery RW, Sherwood NE. Lifestyle patterns associated with diet, physical activity, body mass index and amount of recent weight loss in a sample of successful weight losers. Int J Behav Nutr Phys Act. Jun 26 2012;9:79. doi:10.1186/1479-5868-9-79 22734914 | Study design
204 | Fujiwara T, Nakata R. Skipping breakfast is associated with reproductive dysfunction in post-adolescent female college students. Appetite. Dec 2010;55(3):714–7. doi:10.1016/j.appet.2010.08.005 20728489 | Study design; Intervention/Exposure; Outcome
205 | Fulkerson JA, Friend S, Flattum C, Promoting healthful family meals to prevent obesity: HOME Plus, a randomized controlled trial. Int J Behav Nutr Phys Act. Dec 15 2015;12:154. doi:10.1186/s12966-015-0320-3 26667110 | Intervention/Exposure
206 | Fulkerson JA, Friend S, Horning M, Family Home Food Environment and Nutrition-Related Parent and Child Personal and Behavioral Outcomes of the Healthy Home Offerings viathe Mealtime Environment (HOME) Plus Program: A Randomized Controlled Trial. J Acad Nutr Diet. Feb 2018;118(2):240–251. doi:10.1016/j.jand.2017.04.006 28578900 | Intervention/Exposure
207 | Fulkerson JA, Neumark-Sztainer D, Hannan PJ, Story M. Family meal frequency and weight status among adolescents: cross-sectional and 5-year longitudinal associations. Obesity (Silver Spring). Nov 2008;16(11):2529–34. doi:10.1038/oby.2008.388 18719674 | Intervention/Exposure
208 | Fuller-Tyszkiewicz M, Skouteris H, Hardy LL, Halse C. The associations between TV viewing, food intake, and BMI. A prospective analysis of data from the Longitudinal Study of Australian Children. Appetite. Dec 2012;59(3):945–8. doi:10.1016/j.appet.2012.09.009 23000277 | Intervention/Exposure
209 | Gabel K, Fitzgibbon ML, Yazici C, The basis and design for time-restricted eating compared with daily calorie restriction for weight loss and colorectal cancer risk reduction trial (TRE-CRC trial). Journal article. Obesity (Silver Spring). Dec 2022;30(12):2376–2385. doi:10.1002/oby.23579 36319597 | Intervention/Exposure
210 | Gabel K, Hoddy KK, Burgess HJ, Varady KA. Effect of 8-h time-restricted feeding on sleep quality and duration in adults with obesity. Appl Physiol Nutr Metab. Aug 2019;44(8):903–906. doi:10.1139/apnm-2019-0032 30802152 | Intervention/Exposure
211 | Gabel K, Hoddy KK, Varady KA. Safety of 8-h time restricted feeding in adults with obesity. Appl Physiol Nutr Metab. Jan 2019;44(1):107–109. doi:10.1139/apnm-2018-0389 30216730 | Study design; Intervention/Exposure
212 | Gabel K, Varady KA. Feasibility of Time-Restricted Eating. Obesity (Silver Spring). May 2020;28(5):860. doi:10.1002/oby.22785 | Study design; Intervention/Exposure
213 | Gable S, Chang Y, Krull JL. Television watching and frequency of family meals are predictive of overweight onset and persistence in a national sample of school-aged children. J Am Diet Assoc. Jan 2007;107(1):53–61. doi:10.1016/j.jada.2006.10.010 17197271 | Intervention/Exposure
214 | Gaeini Z, Malmir H, Mirmiran P, Feizy Z, Azizi F. Snack consumption patterns and their associations with risk of incident metabolic syndrome: Tehran lipid and glucose study. Article. Nutrition & Metabolism. Apr 26 2023;20(1)doi:10.1186/s12986-023-00745-0 | Intervention/Exposure
215 | Gage R, Girling-Butcher M, Joe E, The Frequency and Context of Snacking among Children: An Objective Analysis Using Wearable Cameras. Nutrients. Dec 30 2020;13(1)doi:10.3390/nu13010103 | Study design; Outcome
216 | Galfo M, Censi L, D'Addezio L, Melini F, Martone D. Overweight/obesity and lifestyle factors amongItalian adolescents: the ALIADO study. Minerva Pediatr (Torino). Jun 2022;74(3):251–258. doi:10.23736/S2724-5276.16.04708-3 28006896 | Study design
217 | Gallant A, Lundgren J, OĽoughlin J, Night-eating symptoms and 2-year weight change in parentsenrolled in the QUALITY cohort. Int J Obes (Lond). Jul 2015;39(7):1161–5. doi:10.1038/ijo.2015.36 25797608 | Intervention/Exposure
218 | Gamsizkan Z, Onmez A, Sahip Karakas T. Chronobiological evaluation and an intervention study on timing of food intake in the treatment of obesity. Int J Clin Pract. Oct 2021;75(10):e14502. doi:10.1111/ijcp.14502 34117692 | Study design; Intervention/Exposure; Outcome
219 | Gao Y, Tsintzas K, Macdonald IA, Cordon SM, Taylor MA. Effects of intermittent (5:2) or continuous energy restriction on basal and postprandial metabolism: a randomised study in normal-weight, young participants. Eur J Clin Nutr. Jan 2022;76(1):65–73. doi:10.1038/s41430-021-00909-2 34040199 | Intervention/Exposure
220 | Garaulet M, Gomez-Abellan P. Timing of food intake and obesity: a novel association. Article in Press. Physiol Behav. Jul 2014;134:44–50. doi:10.1016/j.physbeh.2014.01.001 24467926 | Intervention/Exposure; Comparator
221 | Garaulet M, Gomez-Abellan P, Alburquerque-Bejar JJ, Lee YC, Ordovas JM, Scheer FA. Timing of food intake predicts weight loss effectiveness. Int J Obes (Lond). Apr 2013;37(4):604–11. doi:10.1038/ijo.2012.229 23357955 | Study design; Intervention/Exposure
222 | Garaulet M, Ortega FB, Ruiz JR, Short sleep duration is associated with increased obesity markersin European adolescents: effect of physical activity and dietary habits. The HELENA study. Int J Obes (Lond). Oct 2011;35(10):1308–17. doi:10.1038/ijo.2011.149 21792170 | Intervention/Exposure
223 | Garaulet M, Vera B, Bonnet-Rubio G, Gomez-Abellan P, Lee YC, Ordovas JM. Lunch eating predicts weight-loss effectiveness in carriers of the common allele at PERILIPIN1: the ONTIME (Obesity, Nutrigenetics, Timing, Mediterranean) study. Am J Clin Nutr. Oct 2016;104(4):1160–1166. doi:10.3945/ajcn.116.134528 27629052 | Intervention/Exposure; Comparator
224 | Gates G, Perera T. Association between Breakfast Consumption and Nutritional Status in 9 to 13 Year Old Children. J Nutr Educ Behav. 2013;45(4 Supplement):S31–S31. doi:10.1016/j.jneb.2013.04.084 | Study design; Publication status
225 | Gavela-Pérez T, Parra-Rodríguez A, Vales-Villamarín C, Relationship between eating habits, sleep patterns and physical activity and the degree of obesity in children and adolescents. Article in Press. Endocrinologia, Diabetes y Nutricion. 2022;doi:10.1016/j.endien.2023.08.001 | Study design
226 | Geliebter A, Astbury NM, Aviram-Friedman R, Yahav E, Hashim S. Skipping breakfast leads to weight loss but also elevated cholesterol compared with consuming daily breakfasts of oat porridge or frosted cornflakes in overweight individuals: a randomised controlled trial. J Nutr Sci. 2014;3:e56. doi:10.1017/jns.2014.51 26101624 | Outcome; Duration
227 | George GC, Hanss-Nuss H, Milani TJ, Freeland-Graves JH. Food choices of low-income womenduring pregnancy and postpartum. J Am Diet Assoc. Jun 2005;105(6):899–907. doi:10.1016/j.jada.2005.03.028 15942539 | Intervention/Exposure; Outcome
228 | Gilardini L, Croci M, Pasqualinotto L, Caffetto K, Invitti C. Dietary Habits and Cardiometabolic Health in Obese Children. Obes Facts. 2015;8(2):101–9. doi:10.1159/000381157 26087840 | Intervention/Exposure
229 | Gilhooly CH, Das SK, Golden JK, Food cravings and energy regulation: the characteristics of craved foods and their relationship with eating behaviors and weight change during6 months of dietary energy restriction. Int J Obes (Lond). Dec 2007;31(12):1849–58. doi:10.1038/sj.ijo.0803672 17593902 | Intervention/Exposure; Comparator
230 | Gladka MM, Le Couteur DG, Simpson SJ. Midnight snacks might shorten your life: lifespan and healthspan advantages of eating less and at the right time. Cardiovasc Res. Mar 17 2023;119(1):e108–e110. doi:10.1093/cvr/cvad018 36690382 | Study design
231 | Gluck ME, Venti CA, Salbe AD, Krakoff J. Nighttime eating: commonly observed and related to weightgain in an inpatient food intake study. Am J Clin Nutr. Oct 2008;88(4):900–5. doi:10.1093/ajcn/88.4.900 18842774 | Intervention/Exposure
232 | Godlin Jeneta J. Effect of breakfast in body mass index among college going students. Article. Journal of Pharmaceutical Sciences and Research. 2016;8(6):545–551. | Study design; Country
233 | Goetz AR, Jindal I, Moreno JP, The roles of sleep and eating patterns in adiposity gain amongpreschool-aged children. Am J Clin Nutr. Nov 2022;116(5):1334–1342. doi:10.1093/ajcn/nqac197 35833269 | Intervention/Exposure
234 | Goetz AR, Jindal I, Moreno JP, The roles of sleep and eating patterns in adiposity gain amongpreschool-aged children. Am J Clin Nutr. Nov 2022;116(5):1334–1342. doi:10.1093/ajcn/nqac197 35833269 | Intervention/Exposure; Duplicate; Other
235 | Gong QH, Li SX, Wang SJ, Li H. Dinner-to-bed time is independently associated with overweight/obesity in Chinese school-aged children. Eating and Weight Disorders-Studies on AnorexiaBulimia and Obesity. Dec 2021;26(8):2657–2663. doi:10.1007/s40519-021-01129-0 | Study design; Intervention/Exposure
236 | Gontijo CA, Balieiro LCT, Teixeira GP, Fahmy WM, Crispim CA, Maia YCP. Higher energy intake at night effects daily energy distribution and contributes to excessive weight gain during pregnancy. Nutrition. Jun 2020;74:110756. doi:10.1016/j.nut.2020.110756 32278857 | Intervention/Exposure
237 | Gontijo CA, Balieiro LCT, Teixeira GP, Fahmy WM, Crispim CA, Maia YCP. Effects of timing of food intake on eating patterns, diet quality and weight gain during pregnancy. Article. Br J Nutr. Apr 28 2020;123(8):922–933. doi:10.1017/S0007114519003398 31902384 | Intervention/Exposure; Comparator
238 | Gonzalez JT, Richardson JD, Chowdhury EA, Molecular adaptations of adipose tissue to 6 weeks of morning fasting vs. daily breakfast consumption in lean and obese adults. J Physiol. Feb 15 2018;596(4):609–622. doi:10.1113/JP275113 29193093 | Intervention/Exposure
239 | Gonzalez-Gonzalez A, Betancourt-Ocampo D, Tavel-Gelrud D, Martinez-Lanz P. Risk eating behaviorsin male and female students: a longitudinal study. Eat Behav. Apr 2014;15(2):252–4. doi:10.1016/j.eatbeh.2014.03.006 24854813 | Outcome
240 | Gorin AA, Phelan S, Wing RR, Hill JO. Promoting long-term weight control: does dieting consistency matter? Int J Obes Relat Metab Disord. Feb 2004;28(2):278–81. doi:10.1038/sj.ijo.0802550 14647183 | Intervention/Exposure
241 | Gow ML, Baur LA, Ho M, Can early weight loss, eating behaviors and socioeconomic factors predict successful weight loss at 12- and 24-months in adolescents with obesity and insulin resistance participating in a randomised controlled trial? Int J Behav Nutr Phys Act. Apr 1 2016;13:43. doi:10.1186/s12966-016-0367-9 27036113 | Intervention/Exposure
242 | Goyal R, Julka S. Impact of breakfast skipping on the health status of the population. Indian J Endocrinol Metab. Sep 2014;18(5):683–7. doi:10.4103/2230-8210.139233 25285286 | Study design; Country
243 | Grant CL, Coates AM, Dorrian J, Timing of food intake during simulated night shift impactsglucose metabolism: A controlled study. Chronobiol Int. 2017;34(8):1003–1013. doi:10.1080/07420528.2017.1335318 28635334 | Outcome
244 | Greene LF, Malpede CZ, Henson CS, Hubbert KA, Heimburger DC, Ard JD. Weight maintenance2 years after participation in a weight loss program promoting low-energy density foods. Obesity (Silver Spring). Oct 2006;14(10):1795–801. doi:10.1038/oby.2006.207 17062810 | Intervention/Exposure
245 | Greenhill C. How effective is time-restricted eating for weight loss? Nat Rev Endocrinol. 2020;16(12):677–677. doi:10.1038/s41574-020-00434-5 33067546 | Study design; Intervention/Exposure
246 | Gregori D, Maffeis C. Snacking and obesity: Urgency of a definition to explore such a relationship. Journal of the American Dietetic Association. Apr 2007;107(4):562–562. doi:10.1016/j.jada.2007.02.025 17383256 | Study design; Publication status
247 | Grimes M, Kuczmarski MF, Bodt BA, Breakfast Habits and Diet Quality in Economically Diverse African American and White Adults. Article. Topics in Clinical Nutrition. 2018;33(3):237–246. doi:10.1097/TIN.0000000000000147 | Study design
248 | Grydeland M, Bergh IH, Bjelland M, Correlates of weight status among Norwegian 11-year-olds: The HEIA study. Bmc Public Health. Dec 6 2012;12(1):1053–1053. doi:10.1186/1471-2458-12-1053 23216675 | Study design
249 | Gu C, Brereton N, Schweitzer A, Metabolic Effects of Late Dinner in Healthy Volunteers-A RandomizedCrossover Clinical Trial. Journal Article; Clinical Trial Protocol. J Clin Endocrinol Metab. Aug 1 2020;105(8):2789–802. doi:10.1210/clinem/dgaa354 32525525 | Intervention/Exposure; Comparator
250 | Gubbels JS, Kremers SPJ, Stafleu A, Goldbohm RA, de Vries NK, Thijs C. Clustering of energy balance-related behaviors in 5-year-old children: Lifestyle patterns and their longitudinal associationwith weight status development in early childhood. Article. International Journal of Behavioral Nutrition and Physical Activity. Jun 21 2012;9doi:10.1186/1479-5868-9-77 | Intervention/Exposure
251 | Gupta CC, Centofanti S, Dorrian J, Subjective Hunger, Gastric Upset, and Sleepiness in Responseto Altered Meal Timing during Simulated Shiftwork. Nutrients. Jun 15 2019;11(6)doi:10.3390/nu11061352 31861566 | Intervention/Exposure; Outcome
252 | Gur EB, Turan GA, Ince O, Effect of Ramadan fasting on metabolic markers, dietary intake and abdominal fat distribution in pregnancy. Hippokratia. Oct-Dec 2015;19(4):298–303.27688692 | Intervention/Exposure
253 | Gustafson CR, Rakhmatullaeva N, Beckford SE, Ammachathram A, Cristobal A, Koehler K. Exercise and the Timing of Snack Choice: Healthy Snack Choice is Reduced in the Post-Exercise State. Article. Nutrients. Dec 2018;10(12)doi:10.3390/nu10121941 | Intervention/Exposure; Comparator
254 | Guvenc A. Effects of ramadan fasting on body composition, aerobic performance and lactate, heart rate and perceptual responses in young soccer players. J Hum Kinet. Sep 2011;29:79–91. doi:10.2478/v10078-011-0042-9 23486092 | Intervention/Exposure
255 | Ha AW, Kim JH, Shin DJ, Eating habits, obesity related behaviors, and effects of Danhak exercise in elderly Koreans. Nutr Res Pract. Aug 2010;4(4):295–302. doi:10.4162/nrp.2010.4.4.295 20827345 | Intervention/Exposure
256 | Haganes KL, Silva CP, Eyjolfsdottir SK, Time-restricted eating and exercise training improve HbA1c and body composition in women with overweight/obesity: A randomized controlledtrial. Cell Metab. Oct 4 2022;34(10):1457–1471 e4. doi:10.1016/j.cmet.2022.09.003 36198292 | Intervention/Exposure
257 | Hajna S, Leblanc PJ, Faught BE, Associations between family eating behaviours and body composition measures in peri-adolescents: results from a community-based study of school-aged children. Can J Public Health. Jan 10 2014;105(1):e15–21. doi:10.17269/cjph.105.4150 24735691 | Intervention/Exposure
258 | Halkjaer J, Tjonneland A, Overvad K, Sorensen TI. Dietary predictors of 5-year changes in waist circumference. J Am Diet Assoc. Aug 2009;109(8):1356–66. doi:10.1016/j.jada.2009.05.015 19631041 | Intervention/Exposure
259 | Harder-Lauridsen NM, Rosenberg A, Benatti FB, Ramadan model of intermittent fasting for 28 d had no major effect on body composition, glucose metabolism, or cognitive functions in healthylean men. Nutrition. May 2017;37:92–103. doi:10.1016/j.nut.2016.12.015 28359370 | Intervention/Exposure
260 | Harding S, Teyhan A, Maynard MJ, Cruickshank JK. Ethnic differences in overweight and obesityin early adolescence in the MRC DASH study: the role of adolescent and parental lifestyle. Int J Epidemiol. Feb 2008;37(1):162–72. doi:10.1093/ije/dym252 18204089 | Study design
261 | Hart CN, Jelalian E, Raynor HA, Early patterns of food intake in an adolescent weight loss trialas predictors of BMI change. Eat Behav. Dec 2010;11(4):217–22. doi:10.1016/j.eatbeh.2010.05.001 20850055 | Intervention/Exposure
262 | Hartman TJ, Masters M, Flanders WD, Self-Reported Eating-Occasion Frequency and Timing are Reproducible and Relatively Valid in the American Cancer Society Cancer PreventionStudy-3 Diet Assessment Substudy. J Nutr. Jan 14 2023;152(12):2827–2836. doi:10.1093/jn/nxac206 36055776 | Study design; Outcome
263 | Hassan BK, Cunha DB, da Veiga GV, Pereira RA, Sichieri R. Changes in breakfast frequency and composition during adolescence: The Adolescent Nutritional Assessment Longitudinal Study, a cohort from Brazil. PLoS One. 2018;13(7):e0200587. doi:10.1371/journal.pone.0200587 30024906 | Outcome
264 | Hatanaka M, Hatamoto Y, Tajiri E, Matsumoto N, Tanaka S, Yoshimura E. An Earlier First Meal TimingAssociates with Weight Loss Effectiveness in A 12-Week Weight Loss Support Program. Nutrients. Jan 7 2022;14(2)doi:10.3390/nu14020249 | Intervention/Exposure; Duplicate; Other
265 | Hatanaka M, Hatamoto Y, Tajiri E, Matsumoto N, Tanaka S, Yoshimura E. An Earlier First Meal Timing Associates with Weight Loss Effectiveness in A 12-Week Weight Loss Support Program. Nutrients. Jan 7 2022;14(2)doi:10.3390/nu14020249 | Intervention/Exposure; Comparator
266 | He M, Wang J, Liang Q, Time-restricted eating with or without low-carbohydrate diet reducesvisceral fat and improves metabolic syndrome: a randomized trial. Journal Article; Clinical Trial Protocol. Cell Rep Med. 2022;3(10):100777. doi:10.1016/j.xcrm.2022.100777 36220069 | Intervention/Exposure
267 | Hebestreit A, Börnhorst C, Barba G, Associations between energy intake, daily food intakeand energy density of foods and BMI z-score in 2–9-year-old European children. Eur J Nutr. 2014;53(2):673–681. doi:10.1007/s00394-013-0575-x 24061347 | Study design; Intervention/Exposure
268 | Heden T, Liu Y, Sims LJ, Influence of Meal Frequency on Postprandial Glycemia and Lipemia in Obese Individuals. Med Sci Sports Exerc. May 2011;43(5):673–673. doi:10.1249/01.MSS.0000401864.68675.ce 20881887 | Outcome
269 | Heden TD, Liu Y, Sims LJ, Meal frequency differentially alters postprandial triacylglycerol and insulin concentrations in obese women. Obesity (Silver Spring). Jan 2013;21(1):123–9. doi:10.1002/oby.20247 23505176 | Publication status
270 | Hermans RC, Herman CP, Larsen JK, Engels RC. Social modeling effects on young women's breakfast intake. J Am Diet Assoc. Dec 2010;110(12):1901–5. doi:10.1016/j.jada.2010.09.007 21111098 | Intervention/Exposure
271 | Hermenegildo Y, Lopez-Garcia E, Garcia-Esquinas E, Perez-Tasigchana RF, Rodriguez-Artalejo F, Guallar-Castillon P. Distribution of energy intake throughout the day and weight gain: a population-based cohort study in Spain. Br J Nutr. Jun 2016;115(11):2003–10. doi:10.1017/S0007114516000891 27044416 | Intervention/Exposure
272 | Hermenegildo-Lopez Y, Donat-Vargas C, Sandoval-Insausti H, A Higher Intake of Energy atDinner Is Associated with Incident Metabolic Syndrome: A Prospective Cohort Study in Older Adults. Nutrients. Aug 30 2021;13(9)doi:10.3390/nu13093035 | Intervention/Exposure
273 | Hibi M, Hari S, Yamaguchi T, Mitsui Y, Kondo S, Katashima M. Effect of Short-Term Increase in Meal Frequency on Glucose Metabolism in Individuals with Normal Glucose Tolerance or Impaired Fasting Glucose: A Randomized Crossover Clinical Trial. Article. Nutrients. Sep 6 2019;11(9)doi:10.3390/nu11092126 | Outcome
274 | Hibi M, Masumoto A, Naito Y, Nighttime snacking reduces whole body fat oxidation and increasesLDL cholesterol in healthy young women. Am J Physiol Regul Integr Comp Physiol. Jan 15 2013;304(2):R94–R101. doi:10.1152/ajpregu.00115.2012 23174861 | Intervention/Exposure; Comparator
275 | Hoddy KK, Kroeger CM, Trepanowski JF, Barnosky A, Bhutani S, Varady KA. Meal timing during alternate day fasting: Impact on body weight and cardiovascular disease risk in obese adults. Obesity (Silver Spring). Dec 2014;22(12):2524–31. doi:10.1002/oby.20909 25251676 | Intervention/Exposure; Duration
276 | Hoertel HA, Will MJ, Leidy HJ. A randomized crossover, pilot study examining the effects of a normal protein vs. high protein breakfast on food cravings and reward signals in overweight/obese "breakfast skipping", late-adolescent girls. Nutr J. Aug 6 2014;13:80. doi:10.1186/1475-2891-13-80 25098557 | Outcome
277 | Hohman EE, Balantekin KN, Birch LL, Savage JS. Dieting is associated with reduced bone mineralaccrual in a longitudinal cohort of girls. BMC Public Health. Nov 22 2018;18(1):1285. doi:10.1186/s12889-018-6206-y 30466435 | Intervention/Exposure; Outcome
278 | Holmback U, Lowden A, Akerfeldt T, The human body may buffer small differences in meal size and timing during a 24-h wake period provided energy balance is maintained. J Nutr. Sep 2003;133(9):2748–55. doi:10.1093/jn/133.9.2748 12949360 | Outcome
279 | Holmstrup ME, Owens CM, Fairchild TJ, Kanaley JA. Effect of meal frequency on glucose and insulin excursions over the course of a day. Article. e-SPEN. 2010;5(6):e277–e280. doi:10.1016/j.eclnm.2010.10.001 | Outcome
280 | Hopkins LC, Sattler M, Steeves EA, Jones-Smith JC, Gittelsohn J. Breakfast Consumption Frequency and Its Relationships to Overall Diet Quality, Using Healthy Eating Index 2010, and BodyMass Index among Adolescents in a Low-Income Urban Setting. Ecol Food Nutr. Jul-Aug 2017;56(4):297–311. doi:10.1080/03670244.2017.1327855 28604287 | Study design
281 | Huang SX, Fu YX, Wang HM, Giang S. Effects of breakfast with different calorigenic amounts on blood glucose, insulin and glucagon levels. J Zhejiang Univ Sci. Nov-Dec 2003;4(6):753–5. doi:10.1631/jzus.2003.0753 14566995 | Outcome; Country
282 | Hunsberger M, Mehlig K, Bornhorst C, Dietary Carbohydrate and Nocturnal Sleep Durationin Relation to Children's BMI: Findings from the IDEFICS Study in Eight European Countries. Nutrients. Dec 8 2015;7(12):10223–36. doi:10.3390/nu7125529 26670249 | Study design
283 | Huseinovic E, Winkvist A, Bertz F, Brekke HK. Changes in food choice during a successful weightloss trial in overweight and obese postpartum women. Obesity (Silver Spring). Dec 2014;22(12):2517–23. doi:10.1002/oby.20895 25234605 | Intervention/Exposure
284 | Hutchison AT, Liu B, Wood RE, Effects of Intermittent Versus Continuous Energy Intakes onInsulin Sensitivity and Metabolic Risk in Women with Overweight. Obesity (Silver Spring). Jan 2019;27(1):50–58. doi:10.1002/oby.22345 30569640 | Intervention/Exposure
285 | Hutchison AT, Regmi P, Manoogian ENC, Time-Restricted Feeding Improves Glucose Tolerance in Men at Risk for Type 2 Diabetes: A Randomized Crossover Trial. Obesity (Silver Spring). May 2019;27(5):724–732. doi:10.1002/oby.22449 31002478 | Intervention/Exposure
286 | Huus K, Brekke HK, Ludvigsson JF, Ludvigsson J. Relationship of food frequencies as reported byparents to overweight and obesity at 5 years. Acta Paediatr. Jan 2009;98(1):139–43. doi:10.1111/j.1651-2227.2008.01043.x 18823298 | Intervention/Exposure
287 | Ibe Y, Miyakawa H, Fuse-Nagase Y, Association of eating three meals irregularly with changes in BMI and weight among young Japanese men and women: A 2-year follow-up. Physiol Behav. Sep 1 2016;163:81–87. doi:10.1016/j.physbeh.2016.04.045 27126967 | Intervention/Exposure
288 | Ishimoto Y, Yoshida M, Nagata K, Yamada H, Hashizume H, Yoshimura N. Consuming breakfast and exercising longer during high school increases bone mineral density in young adultmen. J Bone Miner Metab. May 2013;31(3):329–36. doi:10.1007/s00774-012-0415-8 23263782 | Outcome
289 | Ishizuka R, Otaki N, Tai Y, Breakfast Skipping and Declines in Cognitive Score Among Community-Dwelling Older Adults: A Longitudinal Study of the HEIJO-KYO Cohort. J Geriatr PsychiatryNeurol. Jul 2023;36(4):316–322. doi:10.1177/08919887221135551 | Outcome
290 | Iwasaki T, Hirose A, Azuma T, Association between eating behavior and poor glycemic control in Japanese adults. Sci Rep. Mar 4 2019;9(1):3418. doi:10.1038/s41598-019-39001-y 30833585 | Outcome
291 | Jaaskelainen A, Schwab U, Kolehmainen M, Meal frequencies modify the effect of common genetic variants on body mass index in adolescents of the northern Finland birth cohort1986. PLoS One. 2013;8(9):e73802. doi:10.1371/journal.pone.0073802 24040077 | Study design
292 | Jaaskelainen A, Schwab U, Kolehmainen M, Pirkola J, Jarvelin MR, Laitinen J. Associations of meal frequency and breakfast with obesity and metabolic syndrome traits in adolescents of Northern Finland Birth Cohort 1986. Nutr Metab Cardiovasc Dis. Oct 2013;23(10):1002–9. doi:10.1016/j.numecd.2012.07.006 22901841 | Study design
293 | Jackson SL, Cunningham SA. The stability of children's weight status over time, and the role of television, physical activity, and diet. Article. Prev Med. Jul 2017;100:229–234. doi:10.1016/j.ypmed.2017.04.026 28450122 | Intervention/Exposure
294 | Jacob R, Tremblay A, Panahi S, Provencher V, Drapeau V. Is the timing of food intake a potential indicator of low weight loss responders? A secondary analysis of three weight loss studies. Clin Obes. Jun 2020;10(3):e12360. doi:10.1111/cob.12360 32441491 | Intervention/Exposure
295 | Jacobson IG, Smith TC, Smith B, Disordered eating and weight changes after deployment: longitudinal assessment of a large US military cohort. Am J Epidemiol. Feb 15 2009;169(4):415–27. doi:10.1093/aje/kwn366 19193718 | Intervention/Exposure
296 | Jaeger V, Koletzko B, Luque V, Distribution of energy and macronutrient intakes across eatingoccasions in European children from 3 to 8 years of age: The EU Childhood Obesity Project Study. Eur J Nutr. Feb 2023;62(1):165–174. doi:10.1007/s00394-022-02944-6 35930067 | Intervention/Exposure; Comparator
297 | Jaeger V, Koletzko B, Luque V, Time of Dietary Energy and Nutrient Intake and Body MassIndex in Children: Compositional Data Analysis from the Childhood Obesity Project (CHOP) Trial. Nutrients. Oct 18 2022;14(20)doi:10.3390/nu14204356 | Outcome
298 | Jaeger V, Koletzko B, Luque V, Eating Frequency in European Children from 1 to 96 Months of Age: Results of the Childhood Obesity Project Study. Nutrients. Feb 16 2023;15(4)doi:10.3390/nu15040984 | Intervention/Exposure; Comparator
299 | Jakubowicz D, Barnea M, Wainstein J, Froy O. High caloric intake at breakfast vs. dinner differentially influences weight loss of overweight and obese women. Obesity (Silver Spring). Dec 2013;21(12):2504–12. doi:10.1002/oby.20460 23512957 | Intervention/Exposure; Comparator
300 | Jakubowicz D, Barnea M, Wainstein J, Froy O. Effects of caloric intake timing on insulin resistanceand hyperandrogenism in lean women with polycystic ovary syndrome. Clin Sci (Lond). Nov 2013;125(9):423–32. doi:10.1042/CS20130071 23688334 | Intervention/Exposure; Comparator
301 | Jakubowicz D, Wainstein J, Landau Z, Influences of Breakfast on Clock Gene Expression and Postprandial Glycemia in Healthy Individuals and Individuals With Diabetes: A Randomized ClinicalTrial. Journal Article; Clinical Trial Protocol. Diabetes Care. Nov 2017;40(11):1573– 1579. doi:10.2337/dc16-2753 28830875 | Outcome
302 | Jamshed H, Steger FL, Bryan DR, Effectiveness of Early Time-Restricted Eating for Weight Loss, Fat Loss, and Cardiometabolic Health in Adults With Obesity: A Randomized Clinical Trial. JAMA Intern Med. Sep 1 2022;182(9):953–962. doi:10.1001/jamainternmed.2022.3050 35939311 | Intervention/Exposure
303 | Jansen W, Mackenbach JP, Joosten-van Zwanenburg E, Brug J. Weight status, energy-balance behaviours and intentions in 9–12-year-old inner-city children. J Hum Nutr Diet. Feb 2010;23(1):85–96. doi:10.1111/j.1365-277X.2009.01027.x 20078731 | Study design
304 | Jeffery RW, Abbott G, Ball K, Crawford D. Behavior and weight correlates of weight-control effortsin Australian women living in disadvantage: The READI study. Article. Int J Behav Nutr Phys Act. Apr 26 2013;10:52. doi:10.1186/1479-5868-10-52 23621952 | Intervention/Exposure
305 | Jeffery RW, Rick AM. Cross-sectional and longitudinal associations between body mass index and marriage-related factors. Obes Res. Aug 2002;10(8):809–15. doi:10.1038/oby.2002.109 12181390 | Intervention/Exposure
306 | Johnson BA, Kremer PJ, Swinburn BA, de Silva-Sanigorski AM. Multilevel analysis of the Be Active Eat Well intervention: environmental and behavioural influences on reductions in child obesityrisk. Int J Obes (Lond). Jul 2012;36(7):901–7. doi:10.1038/ijo.2012.23 22531087 | Intervention/Exposure
307 | Johnson SS, Paiva AL, Cummins CO, Transtheoretical model-based multiple behavior intervention for weight management: effectiveness on a population basis. Prev Med. Mar 2008;46(3):238–46. doi:10.1016/j.ypmed.2007.09.010 18055007 | Intervention/Exposure
308 | Jones R, Pabla P, Mallinson J, Two weeks of early time-restricted feeding (eTRF) improves skeletal muscle insulin and anabolic sensitivity in healthy men. Am J Clin Nutr. Oct 1 2020;112(4):1015–1028. doi:10.1093/ajcn/nqaa192 32729615 | Intervention/Exposure
309 | Joseph LS, Gorin AA, Mobley SL, Mobley AR. Impact of a Short-Term Nutrition Education Child CarePilot Intervention on Preschool Children's Intention To Choose Healthy Snacks and Actual Snack Choices. Child Obes. Oct 2015;11(5):513–20. doi:10.1089/chi.2015.0028 26280736 | Intervention/Exposure
310 | Kahleova H, Lloren JI, Mashchak A, Hill M, Fraser GE. Meal Frequency and Timing Are Associatedwith Changes in Body Mass Index in Adventist Health Study 2. J Nutr. Sep 2017;147(9):1722–1728. doi:10.3945/jn.116.244749 28701389 | Study design
311 | Kalam F, Akasheh RT, Cienfuegos S, Effect of time-restricted eating on sex hormone levels in premenopausal and postmenopausal females. Obesity (Silver Spring). Feb 2023;31 Suppl 1(Suppl 1):57–62. doi:10.1002/oby.23562 36203273 | Intervention/Exposure
312 | Kaneko H, Itoh H, Kiriyama H, Possible association between eating behaviors and cardiovascular disease in the general population: Analysis of a nationwide epidemiological database. Atherosclerosis. Mar 2021;320:79–85. doi:10.1016/j.atherosclerosis.2021.01.022 33581389 | Outcome
313 | Kapinos KA, Yakusheva O. Environmental influences on young adult weight gain: evidence froma natural experiment. J Adolesc Health. Jan 2011;48(1):52–8. doi:10.1016/j.jadohealth.2010.05.021 21185524 | Intervention/Exposure
314 | Karatzi K, Georgiopoulos G, Yannakoulia M, Eating frequency predicts new onset hypertension and the rate of progression of blood pressure, arterial stiffness, and wave reflections. J Hypertens. Mar 2016;34(3):429–37; discussion 437. doi:10.1097/HJH.0000000000000822 26771340 | Outcome
315 | Karfopoulou E, Brikou D, Mamalaki E, Dietary patterns in weight loss maintenance: results from the MedWeight study. Eur J Nutr. Apr 2017;56(3):991–1002. doi:10.1007/s00394-015-1147-z 26744302 | Study design
316 | Karras SN, Koufakis T, Adamidou L, Effects of orthodox religious fasting versus combined energyand time restricted eating on body weight, lipid concentrations and glycaemic profile. Int J Food Sci Nutr. Feb 2021;72(1):82–92. doi:10.1080/09637486.2020.1760218 32362210 | Intervention/Exposure
317 | Karras SN, Koufakis T, Adamidou L, Effects of Christian Orthodox Fasting Versus Time-Restricted Eating on Plasma Irisin Concentrations Among Overweight Metabolically Healthy Individuals. Nutrients. Mar 25 2021;13(4)doi:10.3390/nu13041071 | Intervention/Exposure
318 | Karras SN, Koufakis T, Adamidou L, Implementation of Christian Orthodox fasting improves plasma adiponectin concentrations compared with time-restricted eating in overweight premenopausal women. Int J Food Sci Nutr. Mar 2022;73(2):210–220. doi:10.1080/09637486.2021.1941803 34148496 | Intervention/Exposure
319 | Karras SN, Koufakis T, Adamidou L, Similar late effects of a 7-week orthodox religious fasting and a time restricted eating pattern on anthropometric and metabolic profiles of overweightadults. Int J Food Sci Nutr. Mar 2021;72(2):248–258. doi:10.1080/09637486.2020.1787959 32605472 | Intervention/Exposure
320 | Katsuura-Kamano S, Arisawa K, Uemura H, Association of skipping breakfast and short sleep duration with the prevalence of metabolic syndrome in the general Japanese population: Baseline data from the Japan Multi-Institutional Collaborative cohort study. Prev Med Rep. Dec 2021;24:101613. doi:10.1016/j.pmedr.2021.101613 34976669 | Study design
321 | Kawada T, Okada K, Amezawa M. Components of the metabolic syndrome and lifestyle factors in Japanese male workers. Metab Syndr Relat Disord. Dec 2008;6(4):263–6. doi:10.1089/met.2008.0020 19067529 | Study design
322 | Keogh JB, Pedersen E, Petersen KS, Clifton PM. Effects of intermittent compared to continuous energy restriction on short-term weight loss and long-term weight loss maintenance. Clin Obes. Jun 2014;4(3):150–6. doi:10.1111/cob.12052 25826770 | Intervention/Exposure
323 | Kerkadi A, Sadig AH, Bawadi H, The Relationship between Lifestyle Factors and Obesity Indicesamong Adolescents in Qatar. Int J Environ Res Public Health. Nov 13 2019;16(22)doi:10.3390/ijerph16224428 | Study design
324 | Keski-Rahkonen A, Bulik CM, Pietilainen KH, Rose RJ, Kaprio J, Rissanen A. Eating styles, overweight and obesity in young adult twins. Eur J Clin Nutr. Jul 2007;61(7):822–9. doi:10.1038/sj.ejcn.1602601 17251930 | Study design
325 | Kesztyus D, Cermak P, Gulich M, Kesztyus T. Adherence to Time-Restricted Feeding and Impact on Abdominal Obesity in Primary Care Patients: Results of a Pilot Study in a Pre-Post Design. Nutrients. Nov 21 2019;11(12)doi:10.3390/nu11122854 | Study design; Intervention/Exposure
326 | Kesztyus D, Cermak P, Kesztyus T, Barzel A. Early or Delayed Onset of Food Intake in Time-Restricted Eating: Associations with Markers of Obesity in a Secondary Analysis of Two Pilot Studies. Int J Environ Res Public Health. Sep 21 2021;18(18)doi:10.3390/ijerph18189935 | Study design; Intervention/Exposure
327 | Kesztyus D, Vorwieger E, Schonsteiner D, Gulich M, Kesztyus T. Applicability of time-restricted eatingfor the prevention of lifestyle-dependent diseases in a working population: results of a pilot study in a pre-post design. Ger Med Sci. 2021;19:Doc04. doi:10.3205/000291 33911996 | Study design; Intervention/Exposure
328 | Kim H, Yoon E, Kim OY, Kim EM. Short-term Effects of Eating Behavior Modification on Metabolic Syndrome-Related Risks in Overweight and Obese Korean Adults. J Obes Metab Syndr. Mar 30 2022;31(1):70–80. doi:10.7570/jomes21074 35296564 | Intervention/Exposure
329 | Kim HS, Jung SJ, Jang S, Kim MJ, Cha YS. Rice-based breakfast improves fasting glucose and HOMA-IR in Korean adolescents who skip breakfast, but breakfast skipping increases aromatic amino acids associated with diabetes prediction in Korean adolescents who skip breakfast: a randomized, parallel-group, controlled trial. Nutr Res Pract. Aug 2022;16(4):450–463. doi:10.4162/nrp.2022.16.4.450 35919293 | Intervention/Exposure; Comparator
330 | Kim J, Song Y. Early Time-Restricted Eating Reduces Weight and Improves Glycemic Response in Young Adults: A Pre-Post Single-Arm Intervention Study. Obes Facts. 2023;16(1):69–81. doi:10.1159/000527838 36318892 | Study design; Intervention/Exposure
331 | Kim S, DeRoo LA, Sandler DP. Eating patterns and nutritional characteristics associated with sleep duration. Public Health Nutr. May 2011;14(5):889–95. doi:10.1017/S136898001000296X 21029511 | Study design; Outcome
332 | Kirk TR. Role of dietary carbohydrate and frequent eating in body-weight control. Proc Nutr Soc. Aug 2000;59(3):349–58. doi:10.1017/s0029665100000409 10997651 | Study design
333 | Kirsten W. Breakfast. Positive Health. 2010;(177):1–1. | Study design
334 | Kishimoto T, Churiki M, Miyazato T, Yamashiro A, Nagasawa Y, Shokita H. Association between lifestyle and metabolic syndrome incidence of workers in northern Okinawa, Japan: A cohortstudy. Article. Preventive Medicine Reports. Dec 2022;30doi:10.1016/j.pmedr.2022.101995 | Outcome
335 | Klein EG, Lytle LA, Chen V. Social ecological predictors of the transition to overweight in youth: results from the Teens Eating for Energy and Nutrition at Schools (TEENS) study. J Am Diet Assoc. Jul 2008;108(7):1163–9. doi:10.1016/j.jada.2008.04.007 18589024 | Intervention/Exposure
336 | Klohe-Lehman DM, Freeland-Graves J, Clarke KK, Low-income, overweight and obese mothers as agents of change to improve food choices, fat habits, and physical activity in their 1-to-3-year-old children. J Am Coll Nutr. Jun 2007;26(3):196–208. doi:10.1080/07315724.2007.10719602 17634164 | Intervention/Exposure
337 | Kobayashi F, Ogata H, Omi N, Effect of breakfast skipping on diurnal variation of energy metabolism and blood glucose. Obes Res Clin Pract. May-Jun 2014;8(3):e201–98. doi:10.1016/j.orcp.2013.01.001 | Comparator; Outcome
338 | Kohri T, Shimizu A, Suzuki T, Longitudinal Study on Relationships among Snack Energy Intake, Body Mass Index, and Nutrient Intake in Japanese Children Aged 6–7 Years. J Nutr Sci Vitaminol (Tokyo). 2021;67(3):163–169. doi:10.3177/jnsv.67.163 34193675 | Intervention/Exposure
339 | Kong A, Beresford SAA, Alfano CM, Self-monitoring and eating-related behaviors are associatedwith 12-month weight loss in postmenopausal overweight-to-obese women. J Acad Nutr Diet. Sep 2012;112(9):1428–1435. doi:10.1016/j.jand.2012.05.014 22795495 | Study design
340 | Kong A, Beresford SAA, Alfano CM, Associations between Snacking and Weight Loss and Nutrient Intake among Postmenopausal Overweight to Obese Women in a Dietary Weight-Loss Intervention. Journal article. Journal of the American Dietetic Association. Dec 2011;111(12):1898–1903. doi:10.1016/j.jada.2011.09.012 22117666 | Study design
341 | Koopman KE, Caan MW, Nederveen AJ, Hypercaloric diets with increased meal frequency, but not meal size, increase intrahepatic triglycerides: a randomized controlled trial. Hepatology. Aug 2014;60(2):545–53. doi:10.1002/hep.27149 24668862 | Comparator
342 | Kosti RI, Panagiotakos DB, Mihas CC, Dietary habits, physical activity and prevalence of overweight/obesity among adolescents in Greece: the Vyronas study. Med Sci Monit. Oct 2007;13(10):CR437–44.17901850 | Study design
343 | Kotarsky CJ, Johnson NR, Mahoney SJ, Time-restricted eating and concurrent exercise training reduces fat mass and increases lean mass in overweight and obese adults. Physiol Rep. May 2021;9(10):e14868. doi:10.14814/phy2.14868 34042299 | Intervention/Exposure
344 | Kuhlmann KL. Weight change in college freshmen: Personal, interpersonal and situational influences. 2013;(Ph.D.):202 p-202 p. | Study design; Publication status
345 | Lagarde D, Kazak L. The timing of eating controls energy use. Article. Science. Oct 21 2022;378(6617):251–252. doi:10.1126/science.ade6720 36264788 | Study design
346 | Lakkakula AP, Zanovec M, Silverman L, Murphy E, Tuuri G. Black children with high preferencesfor fruits and vegetables are at less risk of being at risk of overweight or overweight. J Am Diet Assoc. Nov 2008;108(11):1912–5. doi:10.1016/j.jada.2008.08.019 18954583 | Study design; Intervention/Exposure
347 | Laramee C, Drapeau V, Valois P, Evaluation of a Theory-Based Intervention Aimed at Reducing Intention to Use Restrictive Dietary Behaviors Among Adolescent Female Athletes. J NutrEduc Behav. Jun 2017;49(6):497–504 e1. doi:10.1016/j.jneb.2017.03.009 | Intervention/Exposure
348 | Larson N, Fulkerson J, Story M, Neumark-Sztainer D. Shared meals among young adults are associated with better diet quality and predicted by family meal patterns during adolescence. Public Health Nutr. May 2013;16(5):883–93. doi:10.1017/S1368980012003539 22857517 | Intervention/Exposure
349 | Larson N, Miller J, Watts A, Story M, Neumark-Sztainer D. What, When, and Where: Measures of Adolescent Snacking Behaviors Are Associated with Dietary Intake and Weight Status. Journal of Adolescent Health. Feb 2016;58(2):S11–S12. doi:10.1016/j.jadohealth.2015.10.038 | Intervention/Exposure; Outcome
350 | Larson N, Wang Q, Berge JM, Shanafelt A, Nanney MS. Eating breakfast together as a family: mealtime experiences and associations with dietary intake among adolescents in rural Minnesota, USA. Public Health Nutr. Jun 2016;19(9):1565–1574. doi:10.1017/S1368980016000379 26973150 | Intervention/Exposure; Outcome
351 | Larson NI, Neumark-Sztainer D, Hannan PJ, Story M. Family meals during adolescence are associated with higher diet quality and healthful meal patterns during young adulthood. J Am DietAssoc. Sep 2007;107(9):1502–10. doi:10.1016/j.jada.2007.06.012 | Publication status
352 | Larson NI, Neumark-Sztainer D, Story M. Weight control behaviors and dietary intake among adolescentsand young adults: longitudinal findings from Project EAT. J Am Diet Assoc. Nov 2009;109(11):1869–77. doi:10.1016/j.jada.2009.08.016 19857628 | Study design; Intervention/Exposure
353 | Laska MN, Lytle LA, Nanney MS, Moe SG, Linde JA, Hannan PJ. Results of a 2-year randomized, controlled obesity prevention trial: Effects on diet, activity and sleep behaviors in anat-risk young adult population. Prev Med. Aug 2016;89:230–236. doi:10.1016/j.ypmed.2016.06.001 27283096 | Intervention/Exposure
354 | Laurson K, Eisenmann JC, Moore S. Lack of association between television viewing, soft drinks, physical activity and body mass index in children. Acta Paediatr. Jun 2008;97(6):795– 800. doi:10.1111/j.1651-2227.2008.00713.x 18410467 | Intervention/Exposure
355 | LeCheminant JD, Christenson E, Bailey BW, Tucker LA. Restricting night-time eating reduces dailyenergy intake in healthy young men: a short-term cross-over study. Br J Nutr. Dec 14 2013;110(11):2108–13. doi:10.1017/S0007114513001359 23702187 | Intervention/Exposure
356 | LeCroy MN, Truesdale KP, Matheson DM, Snacking characteristics and patterns and their associations with diet quality and BMI in the Childhood Obesity Prevention and Treatment Research Consortium. Public Health Nutr. Dec 2019;22(17):3189–3199. doi:10.1017/S1368980019000958 31112114 | Study design
357 | Lee I, Bang KS, Moon H, Kim J. Risk Factors for Obesity Among Children Aged 24 to 80 months in Korea: A Decision Tree Analysis. Journal of Pediatric Nursing-Nursing Care of Children & Families. May-Jun 2019;46:E15–E23. doi:10.1016/j.pedn.2019.02.004 | Study design
358 | Leech RM, McNaughton SA, Crawford DA, Campbell KJ, Pearson N, Timperio A. Family food involvement and frequency of family dinner meals among Australian children aged 10–12years. Cross-sectional and longitudinal associations with dietary patterns. Appetite. Apr 2014;75:64–70. doi:10.1016/j.appet.2013.12.021 24389242 | Intervention/Exposure
359 | Leidy HJ, Armstrong CL, Tang M, Mattes RD, Campbell WW. The influence of higher protein intakeand greater eating frequency on appetite control in overweight and obese men. Obesity (Silver Spring). Sep 2010;18(9):1725–32. doi:10.1038/oby.2010.45 20339363 | Outcome
360 | Lemmens SG, Martens EA, Born JM, Martens MJ, Westerterp-Plantenga MS. Staggered meal consumptionfacilitates appetite control without affecting postprandial energy intake. J Nutr. Mar 2011;141(3):482–8. doi:10.3945/jn.110.133264 21270370 | Intervention/Exposure
361 | Leong SL, Gray A, Haszard J, Horwath C. Weight-Control Methods, 3-Year Weight Change, and Eating Behaviors: A Prospective Nationwide Study of Middle-Aged New Zealand Women. J AcadNutr Diet. Aug 2016;116(8):1276–84. doi:10.1016/j.jand.2016.02.021 | Intervention/Exposure
362 | Leung GKW, Davis R, Huggins CE, Ware RS, Bonham MP. Does rearranging meal times at night improve cardiovascular risk factors? An Australian pilot randomised trial in night shift workers. Nutr Metab Cardiovasc Dis. Jun 7 2021;31(6):1890–1902. doi:10.1016/j.numecd.2021.03.008 33994064 | Intervention/Exposure; Duration
363 | Levitsky DA, Halbmaier CA, Mrdjenovic G. The freshman weight gain: a model for the study of the epidemic of obesity. Int J Obes Relat Metab Disord. Nov 2004;28(11):1435–42. doi:10.1038/sj.ijo.0802776 15365585 | Study design
364 | Levy J. The Breakfast Rush. Health. 2019;33(7):53–56. | Study design
365 | Li C, Xing C, Zhang J, Zhao H, Shi W, He B. Eight-hour time-restricted feeding improves endocrineand metabolic profiles in women with anovulatory polycystic ovary syndrome. J Transl Med. Apr 13 2021;19(1):148. doi:10.1186/s12967-021-02817-2 33849562 | Intervention/Exposure
366 | Li F, Harmer P, Cardinal BJ, Built environment and 1-year change in weight and waist circumference in middle-aged and older adults: Portland Neighborhood Environment and HealthStudy. Am J Epidemiol. Feb 15 2009;169(4):401–8. doi:10.1093/aje/kwn398 19153214 | Intervention/Exposure
367 | Li LB, Wang N, Wu XL, Energy Balance-related Behaviors Are Related to Cardiometabolic Parameters and Predict Adiposity in 8–14-year-old Overweight Chinese ChildrenOne Year Later. Biomed Environ Sci. Oct 2016;29(10):754–757. doi:10.3967/bes2016.100 27927275 | Intervention/Exposure
368 | Likhitweerawong N, Boonchooduang N, Kittisakmontri K, Chonchaiya W, Louthrenoo O. Effectiveness of mobile application on changing weight, healthy eating habits, and quality of life in children and adolescents with obesity: a randomized controlled trial. BMC Pediatr. Nov 10 2021;21(1):499. doi:10.1186/s12887-021-02980-x 34758761 | Intervention/Exposure
369 | Lin D, Chen DD, Huang J, Li Y, Wen XS, Shi HJ. Longitudinal association between the timing of adiposity peak and rebound and overweight at seven years of age. Bmc Pediatrics. Apr 19 2022;22(1):1–13. doi:10.1186/s12887-022-03190-9 34980043 | Study design
370 | Lin TT, Guo YL, Gordon CJ, Snacking among shiftwork nurses related to non-optimal dietary intake. J Adv Nurs. Nov 2022;78(11):3629–3640. doi:10.1111/jan.15253 35429043 | Study design; Outcome
371 | Lin YJ, Wang YT, Chan LC, Chu NF. Effect of time-restricted feeding on body composition and cardio-metabolic risk in middle-aged women in Taiwan. Nutrition. Jan 2022;93:111504. doi:10.1016/j.nut.2021.111504 34763309 | Intervention/Exposure
372 | Linne Y, Dye L, Barkeling B, Rossner S. Weight development over time in parous women--the SPAWN study--15 years follow-up. Int J Obes Relat Metab Disord. Dec 2003;27(12):1516–22. doi:10.1038/sj.ijo.0802441 14634683 | Intervention/Exposure
373 | Liu B, Hutchison AT, Thompson CH, Lange K, Heilbronn LK. Markers of adipose tissue inflammation are transiently elevated during intermittent fasting in women who are overweight orobese. Obes Res Clin Pract. Jul-Aug 2019;13(4):408–415. doi:10.1016/j.orcp.2019.07.001 31302012 | Intervention/Exposure
374 | Liu B, Hutchison AT, Thompson CH, Wittert GA, Heilbronn LK. Weight loss and tissue remodelling following 8-week calorie restriction or intermittent fasting in females who are overweightand obese. Obesity Research & Clinical Practice. 2019;13(1):43–43. doi:10.1016/j.orcp.2016.10.058 | Intervention/Exposure; Publication status
375 | Lobene AJ, Panda S, Mashek DG, Manoogian ENC, Hill Gallant KM, Chow LS. Time-Restricted Eating for 12 Weeks Does Not Adversely Alter Bone Turnover in Overweight Adults. Nutrients. Mar 31 2021;13(4)doi:10.3390/nu13041155 | Intervention/Exposure
376 | Lombardo M, Bellia A, Padua E, Morning meal more efficient for fat loss in a 3-month lifestyle intervention. J Am Coll Nutr. 2014;33(3):198–205. doi:10.1080/07315724.2013.863169 24809437 | Intervention/Exposure; Comparator
377 | Loo RSX, Yap F, Ku CW, Maternal meal irregularities during pregnancy and lifestyle correlates. Appetite. Jan 1 2022;168:105747. doi:10.1016/j.appet.2021.105747 34637771 | Study design; Intervention/Exposure; Outcome
378 | Lotti S, Pagliai G, Asensi MT, Morning chronotype is associated with higher adherence to the Mediterranean diet in a sample of Italian adults. Nutr Metab Cardiovasc Dis. Sep 2022;32(9):2086–2092. doi:10.1016/j.numecd.2022.05.023 35752541 | Intervention/Exposure
379 | Lowe DA, Wu N, Rohdin-Bibby L, Effects of Time-Restricted Eating on Weight Loss and Other Metabolic Parameters in Women and Men With Overweight and Obesity: The TREAT RandomizedClinical Trial. Journal Article; Clinical Trial Protocol. JAMA Intern Med. Nov 1 2020;180(11):1491–1499. doi:10.1001/jamainternmed.2020.4153 32986097 | Intervention/Exposure
380 | Lowe MR, Annunziato RA, Markowitz JT, Multiple types of dieting prospectively predict weight gain during the freshman year of college. Appetite. Jul 2006;47(1):83–90. doi:10.1016/j.appet.2006.03.160 16650913 | Intervention/Exposure
381 | Loy SL, Cheng TS, Colega MT, Predominantly night-time feeding and maternal glycaemic levelsduring pregnancy. Br J Nutr. May 2016;115(9):1563–1570. doi:10.1017/S0007114516000441 26949026 | Intervention/Exposure; Comparator
382 | Lu XJ, Fan ZH, Liu AN, Liu R, Lou XL, Hu JH. Extended Inter-Meal Interval Negatively Impactedthe Glycemic and Insulinemic Responses after Both Lunch and Dinner in Healthy Subjects. Article. Nutrients. Sep 2022;14(17)doi:10.3390/nu14173617 | Intervention/Exposure; Comparator
383 | Lucassen EA, Zhao X, Rother KI, Evening chronotype is associated with changes in eating behavior, more sleep apnea, and increased stress hormones in short sleeping obese individuals. PLoS One. 2013;8(3):e56519. doi:10.1371/journal.pone.0056519 23483886 | Study design; Intervention/Exposure
384 | Lundgren JD, Smith BM, Spresser C, Harkins P, Zolton L, Williams K. The relationship of night eating to oral health and obesity in community dental clinic patients. Gen Dent. May-Jun 2010;58(3):e134–9.20478791 | Study design; Outcome
385 | Lynch S, Johnston JD, Robertson MD. Early versus late time‐restricted feeding in adults at increasedrisk of developing type 2 diabetes: Is there an optimal time to eat for metabolic health? Nutrition Bulletin. 2021;46(1):69–76. doi:10.1111/nbu.12479 | Intervention/Exposure
386 | Lyzwinski LN, Caffery L, Bambling M, Edirippulige S. The Mindfulness App Trial for Weight, Weight-Related Behaviors, and Stress in University Students: Randomized Controlled Trial. JMIR Mhealth Uhealth. Apr 10 2019;7(4):e12210. doi:10.2196/12210 30969174 | Intervention/Exposure
387 | Ma Y, Bertone ER, Stanek EJ, 3rd, Association between eating patterns and obesity in a free-living US adult population. Am J Epidemiol. Jul 1 2003;158(1):85–92. doi:10.1093/aje/kwg117 12835290 | Study design
388 | Madjd A, Taylor MA, Delavari A, Malekzadeh R, Macdonald IA, Farshchi HR. Beneficial effect of high energy intake at lunch rather than dinner on weight loss in healthy obese women in a weight-loss program: a randomized clinical trial. Am J Clin Nutr. Oct 2016;104(4):982–989. doi:10.3945/ajcn.116.134163 27581472 | Comparator
389 | Madjd A, Taylor MA, Delavari A, Malekzadeh R, Macdonald IA, Farshchi HR. Effects of consuming later evening meal v. earlier evening meal on weight loss during a weight loss diet: a randomised clinical trial. Br J Nutr. Aug 28 2021;126(4):632–640. doi:10.1017/S0007114520004456 33172509 | Intervention/Exposure; Comparator
390 | Madkour MI, Malhab LJB, Abdel-Rahman WM, Abdelrahim DN, Saber-Ayad M, Faris ME. Ramadan Diurnal Intermittent Fasting Is Associated With Attenuated FTO Gene Expression in Subjects With Overweight and Obesity: A Prospective Cohort Study. Front Nutr. 2021;8:741811. doi:10.3389/fnut.2021.741811 35372458 | Intervention/Exposure
391 | Maffeis C, Grezzani A, Perrone L, Del Giudice EM, Saggese G, Tato L. Could the savory taste ofsnacks be a further risk factor for overweight in children? J Pediatr Gastroenterol Nutr. Apr 2008;46(4):429–37. doi:10.1097/MPG.0b013e318163b850 18367957 | Study design
392 | Magee CA, Caputi P, Iverson DC. Patterns of health behaviours predict obesity in Australian children. J Paediatr Child Health. Apr 2013;49(4):291–6. doi:10.1111/jpc.12163 23574555 | Intervention/Exposure
393 | Magnusson MB, Hulthen L, Kjellgren KI. Obesity, dietary pattern and physical activity among childrenin a suburb with a high proportion of immigrants. J Hum Nutr Diet. Jun 2005;18(3):187–94. doi:10.1111/j.1365-277X.2005.00604.x 15882381 | Study design
394 | Mahmood L, Gonzalez-Gil EM, Makrilakis K, Cross-sectional and longitudinal associations between family meals frequency and children's overweight/obesity in families at high risk of type2 diabetes: The Feel4Diabetes-study. Pediatr Obes. Apr 2023;18(4):e13000. doi:10.1111/ijpo.13000 36632012 | Intervention/Exposure
395 | Makarem N, Sears DD, St-Onge MP, Variability in Daily Eating Patterns and Eating Jetlag Are Associated With Worsened Cardiometabolic Risk Profiles in the American Heart Association Go Red for Women Strategically Focused Research Network. J Am Heart Assoc. Sep 21 2021;10(18):e022024. doi:10.1161/JAHA.121.022024 34482703 | Intervention/Exposure
396 | Mallan KM, Nambiar S, Magarey AM, Daniels LA. Satiety responsiveness in toddlerhood predicts energy intake and weight status at four years of age. Appetite. Mar 2014;74:79–85. doi:10.1016/j.appet.2013.12.001 24316574 | Intervention/Exposure
397 | Manoogian ENC, Zadourian A, Lo HC, Feasibility of time-restricted eating and impacts on cardiometabolic health in 24-h shift workers: The Healthy Heroes randomized control trial. Article. Cell Metab. Oct 4 2022;34(10):1442–1456 e7. doi:10.1016/j.cmet.2022.08.018 36198291 | Study design; Intervention/Exposure
398 | Mansoori A, Khosravi M, Asadi M. Effects of evening meal timing on weight loss: A pilot open-labelled randomized clinical trial. Article. Journal of Advances in Medical and Biomedical Research. 2020;28(126):41–46. doi:10.30699/jambs.28.126.41 | Intervention/Exposure; Comparator
399 | Marinac CR, Quante M, Mariani S, Associations Between Timing of Meals, Physical Activity, Light Exposure, and Sleep With Body Mass Index in Free-Living Adults. J Phys Act Health. Mar 1 2019;16(3):214–221. doi:10.1123/jpah.2017-0389 30798690 | Study design
400 | Martens CR, Rossman MJ, Mazzo MR, Short-term time-restricted feeding is safe and feasible in non-obese healthy midlife and older adults. Journal article. Geroscience. Apr 2020;42(2):667–686. doi:10.1007/s11357-020-00156-6 31975053 | Intervention/Exposure; Comparator
401 | Martin L. Is Breakfast Related To Total Daily Calorie Intake And BMI In Middle School Latino Adolescents? Med Sci Sports Exerc. 2011;43:507–507. doi:10.1249/01.MSS.0000401397.01546.a9 | Intervention/Exposure
402 | Martinez-Lozano N, Tvarijonaviciute A, Rios R, Baron I, Scheer F, Garaulet M. Late Eating Is Associated with Obesity, Inflammatory Markers and Circadian-Related Disturbances in School-Aged Children. Nutrients. Sep 21 2020;12(9)doi:10.3390/nu12092881 | Study design; Publication status
403 | Martyn-Nemeth P, Hayman LL. Dietary Patterns and Meal Timing to Achieve a Healthy Body Weightand Promote Cardiometabolic Health: What Is the Evidence? J Cardiovasc Nurs. Jan-Feb 01 2023;38(1):3–5. doi:10.1097/JCN.0000000000000954 36260843 | Study design
404 | Maughan RJ, Bartagi Z, Dvorak J, Zerguini Y. Dietary intake and body composition of football playersduring the holy month of Ramadan. J Sports Sci. Dec 2008;26 Suppl 3:S29–38. doi:10.1080/02640410802409675 19085450 | Intervention/Exposure
405 | Maukonen M, Kanerva N, Partonen T, The associations between chronotype, a healthy diet and obesity. Chronobiol Int. 2016;33(8):972–81. doi:10.1080/07420528.2016.1183022 27246115 | Intervention/Exposure
406 | Maukonen M, Kanerva N, Partonen T, Chronotype differences in timing of energy and macronutrient intakes: A population-based study in adults. Obesity (Silver Spring). Mar 2017;25(3):608–615. doi:10.1002/oby.21747 28229553 | Study design; Intervention/Exposure
407 | Maukonen M, Kanerva N, Partonen T, Mannisto S. Chronotype and energy intake timing in relation to changes in anthropometrics: a 7-year follow-up study in adults. Chronobiol Int. Jan 2019;36(1):27–41. doi:10.1080/07420528.2018.1515772 30212231 | Study design; Intervention/Exposure
408 | Mayra ST, Chondropoulos K, De Leon A, Kravat N, Johnston CS. The feasibility and preliminary efficacy of early time-restricted eating on diet quality in college students: A randomizedstudy. Obes Res Clin Pract. Sep-Oct 2022;16(5):413–420. doi:10.1016/j.orcp.2022.08.009 36241590 | Intervention/Exposure
409 | Mayra ST, Kravat N, Chondropoulos K, De Leon A, Johnston CS. Early time-restricted eating may favorably impact cognitive acuity in university students: a randomized pilot study. Article. Nutr Res. Dec 2022;108:1–8. doi:10.1016/j.nutres.2022.10.002 36351326 | Intervention/Exposure
410 | Mazri FH, Manaf ZA, Shahar S, Ludin AFM, Basir SMA. Development and Evaluation of Integrated Chrono-Nutrition Weight Reduction Program among Overweight/Obese with Morning and Evening Chronotypes. Article. International Journal of Environmental Research and Public Health. Apr 2022;19(8)doi:10.3390/ijerph19084469 | Intervention/Exposure
411 | Mazri FH, Manaf ZA, Shahar S, Mat Ludin AF, Karim NA. Improvement in chrono-nutrition is associated with robust weight loss outcomes: An extension of the feasibility study. Chronobiol Int. Mar 2023;40(3):272–283. doi:10.1080/07420528.2023.2165092 36803265 | Study design; Intervention/Exposure
412 | Mazri FH, Manaf ZA, Shahar S, Do Temporal Eating Patterns Differ in Healthy versus Unhealthy Overweight/Obese Individuals? Nutrients. Nov 17 2021;13(11)doi:10.3390/nu13114121 | Intervention/Exposure; Comparator
413 | McConahy KL, Smiciklas-Wright H, Birch LL, Mitchell DC, Picciano MF. Food portions are positivelyrelated to energy intake and body weight in early childhood. J Pediatr. Mar 2002;140(3):340–7. doi:10.1067/mpd.2002.122467 11953733 | Study design; Intervention/Exposure
414 | McCrory MA, Howarth NC, Roberts SB, Huang TT. Eating frequency and energy regulation in free-living adults consuming self-selected diets. J Nutr. Jan 2011;141(1):148–53. doi:10.3945/jn.109.114991 21123466 | Study design
415 | McKiernan F, Hollis JH, Mattes RD. Short-term dietary compensation in free-living adults. Physiol Behav. Mar 18 2008;93(4–5):975–83. doi:10.1016/j.physbeh.2007.12.014 18261752 | Intervention/Exposure
416 | McNeil J, Lamothe G, Cameron JD, Investigating predictors of eating: is resting metabolic ratereally the strongest proxy of energy intake? Am J Clin Nutr. Nov 2017;106(5):1206–1212. doi:10.3945/ajcn.117.153718 28877891 | Intervention/Exposure
417 | Mekary RA, Giovannucci E, Cahill L, Willett WC, van Dam RM, Hu FB. Eating patterns and type 2 diabetes risk in older women: breakfast consumption and eating frequency. Am J Clin Nutr. Aug 2013;98(2):436–43. doi:10.3945/ajcn.112.057521 23761483 | Outcome
418 | Mennella JA, Smethers AD, Decker JE, Delahanty MT, Stallings VA, Trabulsi JC. Effects of Early Weight Gain Velocity, Diet Quality, and Snack Food Access on Toddler Weight Status at 1.5 Years: Follow-Up of a Randomized Controlled Infant Formula Trial. Nutrients. Nov 4 2021;13(11)doi:10.3390/nu13113946 | Intervention/Exposure
419 | Meyer AM, Evenson KR, Couper DJ, Stevens J, Pereria MA, Heiss G. Television, physical activity, diet, and body weight status: the ARIC cohort. Int J Behav Nutr Phys Act. Dec 17 2008;5:68. doi:10.1186/1479-5868-5-68 19091124 | Intervention/Exposure
420 | Meyer U, Schindler C, Bloesch T, Combined impact of negative lifestyle factors on cardiovascular risk in children: a randomized prospective study. J Adolesc Health. Dec 2014;55(6):790–5. doi:10.1016/j.jadohealth.2014.07.007 25249036 | Intervention/Exposure; Outcome
421 | Mielke RT. Determinants of excessive gestational weight gain in Mexican American women in Los Angeles. Dissertation. Azusa Pacific University; 2010. https://search.ebscohost.com/login.aspx?direct=true&db=jlh&AN=109854430&site=ehost-live | Study design
422 | Miller DP. Associations between the home and school environments and child body mass index. Article. Social Science & Medicine. Mar 2011;72(5):677–684. doi:10.1016/j.socscimed.2010.12.003 21227558 | Intervention/Exposure
423 | Milsom VA, Middleton KM, Perri MG. Successful long-term weight loss maintenance in a rural population. Clin Interv Aging. 2011;6:303–9. doi:10.2147/CIA.S25389 22162646 | Study design
424 | Min C, Noh H, Kang YS, Skipping breakfast is associated with diet quality and metabolic syndrome risk factors of adults. Nutr Res Pract. Oct 2011;5(5):455–63. doi:10.4162/nrp.2011.5.5.455 22125684 | Study design
425 | Mindru DE, Moraru E. Risk factors and their implications in the epidemiology of pediatric obesity. Rev Med Chir Soc Med Nat Iasi. Jul-Sep 2012;116(3):739–45.23272520 | Intervention/Exposure
426 | Mirmiran P, Aghayan M, Bakhshi B, Hosseinpour-Niazi S, Azizi F. Socioeconomic status and lifestylefactors modifies the association between snack foods intake and incidence of metabolic syndrome. Nutr J. Jul 22 2021;20(1):70. doi:10.1186/s12937-021-00728-y 34294103 | Intervention/Exposure; Outcome
427 | Mirmiran P, Bahadoran Z, Delshad H, Azizi F. Effects of energy-dense nutrient-poor snacks on the incidence of metabolic syndrome: a prospective approach in Tehran Lipid and Glucose Study. Nutrition. May 2014;30(5):538–43. doi:10.1016/j.nut.2013.09.014 24508464 | Intervention/Exposure; Outcome
428 | Mirzaei A, Ghofranipour F, Ghazanfar ZI. School children's breakfast consumption: An educational intervention based on social cognitive theory. Article. Annals of Tropical Medicine andPublic Health. 2018;(1.2 Special Issue):SP36. | Intervention/Exposure; Outcome
429 | Mizutani T, Suzuki K, Kondo N, Yamagata Z. Association of maternal lifestyles including smokingduring pregnancy with childhood obesity. Obesity (Silver Spring). Dec 2007;15(12):3133–9. doi:10.1038/oby.2007.373 18198324 | Intervention/Exposure; Outcome; Other
430 | Mogensen CS, Faerch K, Bruhn L, Timing and Frequency of Daily Energy Intake in Adults withPrediabetes and Overweight or Obesity and Their Associations with Body Fat. Nutrients. Nov 13 2020;12(11)doi:10.3390/nu12113484 | Study design
431 | Mok A, Haldar S, Lee JCY, Leow MKS, Henry CJ. Postprandial changes in cardiometabolic disease risk in young Chinese men following isocaloric high or low protein diets, stratified by eitherhigh or low meal frequency - a randomized controlled crossover trial. Nutrition Journal. Mar 15 2016;15:1–10. doi:10.1186/s12937-016-0141-5 26728196 | Outcome
432 | Molina-Montes E, Rodríguez-Barranco M, Ching-López A, Circadian clock gene variants and their link with chronotype, chrononutrition, sleeping patterns and obesity in the European prospectiveinvestigation into cancer and nutrition (EPIC) study. Clinical Nutrition. Sep 2022;41(9):1977–1990. doi:10.1016/j.clnu.2022.07.027 35961261 | Intervention/Exposure
433 | Montero MD, Sevilla-Lorente R, Merchan-Ramirez E, 35-LB: Effects of Three Different 8h Time-Restricted Eating Schedules over 4 Weeks on Body Weight and Waist/Hip Circumferences in Adults with Overweight/Obesity: A Pilot Randomized Trial. Diabetes. 2021;70:N.PAG-N.PAG. doi:10.2337/db21-35-LB | Intervention/Exposure; Publication status
434 | Moran LJ, Brown WJ, McNaughton S, Joham AE, Teede HJ. Weight management practices associated with polycystic ovary syndrome and their relationships with diet and physical activity. Obesity Research & Clinical Practice. 2019;13(1):49–50. doi:10.1016/j.orcp.2016.10.067 | Study design; Publication status
435 | Moreno LA, Kersting M, de Henauw S, How to measure dietary intake and food habits in adolescence: the European perspective. Int J Obes (Lond). Sep 2005;29 Suppl 2:S66–77. doi:10.1038/sj.ijo.0803063 16385756 | Study design; Intervention/Exposure
436 | Morgan LM, Shi JW, Hampton SM, Frost G. Effect of meal timing and glycaemic index on glucosecontrol and insulin secretion in healthy volunteers. Br J Nutr. Oct 2012;108(7):1286–91. doi:10.1017/S0007114511006507 22176632 | Intervention/Exposure; Comparator
437 | Moro T, Tinsley G, Longo G, Time-restricted eating effects on performance, immune function, and body composition in elite cyclists: a randomized controlled trial. Journal Article; Clinical Trial Protocol. J Int Soc Sports Nutr. Dec 11 2020;17(1):65. doi:10.1186/s12970-020-00396-z 33308259 | Intervention/Exposure
438 | Moro T, Tinsley G, Pacelli FQ, Marcolin G, Bianco A, Paoli A. Twelve Months of Time-restricted Eating and Resistance Training Improves Inflammatory Markers and Cardiometabolic Risk Factors. Med Sci Sports Exerc. Dec 1 2021;53(12):2577–2585. doi:10.1249/MSS.0000000000002738 34649266 | Intervention/Exposure
439 | Morris A. Breakfast not beneficial for weight loss. Nat Rev Endocrinol. Apr 2019;15(4):190. doi:10.1038/s41574-019-0182-x | Study design
440 | Morris MA, Hutchinson J, Gianfrancesco C, Relationship of the Frequency, Distribution, and Content of Meals/Snacks to Glycaemic Control in Gestational Diabetes: The myfood24 GDM Pilot Study. Nutrients. Dec 18 2019;12(1)doi:10.3390/nu12010003 | Outcome
441 | Mota MC, Waterhouse J, De-Souza DA, Association between chronotype, food intake and physical activity in medical residents. Chronobiol Int. 2016;33(6):730–9. doi:10.3109/07420528.2016.1167711 27096153 | Study design
442 | Mou Y, Jansen PW, Raat H, Nguyen AN, Voortman T. Associations of family feeding and mealtime practices with children's overall diet quality: Results from a prospective population-based cohort. Appetite. May 1 2021;160:105083. doi:10.1016/j.appet.2020.105083 33359227 | Outcome
443 | Mouchacca J, Abbott GR, Ball K. Associations between psychological stress, eating, physical activity, sedentary behaviours and body weight among women: a longitudinal study. BMC Public Health. Sep 11 2013;13:828. doi:10.1186/1471-2458-13-828 24020677 | Intervention/Exposure
444 | Mrdjenovic G, Levitsky DA. Children eat what they are served: the imprecise regulation of energy intake. Appetite. Jun 2005;44(3):273–82. doi:10.1016/j.appet.2005.01.005 15927729 | Study design
445 | Munoz JSG, Canavate R, Hernandez CM, Cara-Salmeron V, Morante JJH. The association amongchronotype, timing of food intake and food preferences depends on body mass status. Eur J Clin Nutr. Jun 2017;71(6):736–742. doi:10.1038/ejcn.2016.182 27650874 | Intervention/Exposure
446 | Munsters MJ, Saris WH. Effects of meal frequency on metabolic profiles and substrate partitioning in lean healthy males. PLoS One. 2012;7(6):e38632. doi:10.1371/journal.pone.0038632 22719910 | Outcome; Duration
447 | Muthayya S, Thomas T, Srinivasan K, Consumption of a mid-morning snack improves memorybut not attention in school children. Physiol Behav. Jan 30 2007;90(1):142–50. doi:10.1016/j.physbeh.2006.09.025 17081574 | Comparator; Outcome
448 | Nagata JM, Braudt DB, Domingue BW, Genetic risk, body mass index, and weight control behaviors: Unlocking the triad. Int J Eat Disord. Jul 2019;52(7):825–833. doi:10.1002/eat.23083 30994932 | Intervention/Exposure
449 | Nagata JM, Garber AK, Tabler J, Murray SB, Vittinghoff E, Bibbins-Domingo K. Disordered eatingbehaviors and cardiometabolic risk among young adults with overweight or obesity. Int J Eat Disord. Aug 2018;51(8):931–941. doi:10.1002/eat.22927 30030944 | Intervention/Exposure; Outcome
450 | Nagata JM, Garber AK, Tabler JL, Murray SB, Bibbins-Domingo K. Differential Risk Factors for UnhealthyWeight Control Behaviors by Sex and Weight Status Among U.S. Adolescents. J Adolesc Health. Sep 2018;63(3):335–341. doi:10.1016/j.jadohealth.2018.03.022 30236999 | Intervention/Exposure
451 | Nagata K, Yoshida M, Ishimoto Y, Hashizume H, Yamada H, Yoshimura N. Skipping breakfast andless exercise are risk factors for bone loss in young Japanese adults: a 3-year follow-up study. J Bone Miner Metab. Jul 2014;32(4):420–7. doi:10.1007/s00774-013-0510-5 24052206 | Outcome
452 | Nakajima K, Higuchi R, Mizusawa K. Unexpectedly High Prevalence of Breakfast Skipping in Low Body-Weight Middle-Aged Men: Results of the Kanagawa Investigation of Total Checkup Data from the National Data Base-7 (KITCHEN-7). Nutrients. Dec 30 2020;13(1)doi:10.3390/nu13010102 | Study design
453 | Nas A, Mirza N, Hagele F, Impact of breakfast skipping compared with dinner skipping on regulationof energy balance and metabolic risk. Am J Clin Nutr. Jun 2017;105(6):1351–1361. doi:10.3945/ajcn.116.151332 28490511 | Comparator; Outcome
454 | Nascimento M, Silva D, Ribeiro S, Nunes M, Almeida M, Mendes-Netto R. Effect of a Nutritional Intervention in Athlete's Body Composition, Eating Behaviour and Nutritional Knowledge: A Comparison between Adults and Adolescents. Nutrients. Sep 7 2016;8(9)doi:10.3390/nu8090535 | Intervention/Exposure
455 | Naska A, Orfanos P, Trichopoulou A, Eating out, weight and weight gain. A cross-sectional and prospective analysis in the context of the EPIC-PANACEA study. Int J Obes (Lond). Mar 2011;35(3):416–26. doi:10.1038/ijo.2010.142 20661252 | Intervention/Exposure
456 | Nederkoorn C, Houben K, Hofmann W, Roefs A, Jansen A. Control yourself or just eat what you like? Weight gain over a year is predicted by an interactive effect of response inhibition and implicit preference for snack foods. Health Psychol. Jul 2010;29(4):389–93. doi:10.1037/a0019921 20658826 | Intervention/Exposure
457 | Nelson MC, Gordon-Larsen P, North KE, Adair LS. Body mass index gain, fast food, and physicalactivity: effects of shared environments over time. Obesity (Silver Spring). Apr 2006;14(4):701–9. doi:10.1038/oby.2006.80 16741273 | Intervention/Exposure
458 | Neuhouser ML, Patterson RE, Kristal AR, Do consumers of savory snacks have poor-quality diets? J Am Diet Assoc. May 2000;100(5):576–9. doi:10.1016/S0002-8223(00)00176-0 10812386 | Study design; Intervention/Exposure
459 | Neumark-Sztainer D, Eisenberg ME, Fulkerson JA, Story M, Larson NI. Family meals and disorderedeating in adolescents: longitudinal findings from project EAT. Arch Pediatr Adolesc Med. Jan 2008;162(1):17–22. doi:10.1001/archpediatrics.2007.9 18180407 | Intervention/Exposure; Outcome
460 | Neumark-Sztainer D, Wall M, Guo J, Story M, Haines J, Eisenberg M. Obesity, disordered eating, and eating disorders in a longitudinal study of adolescents: how do dieters fare 5 years later? J Am Diet Assoc. Apr 2006;106(4):559–68. doi:10.1016/j.jada.2006.01.003 16567152 | Intervention/Exposure
461 | Neumark-Sztainer D, Wall M, Haines J, Story M, Eisenberg ME. Why does dieting predict weight gain in adolescents? Findings from project EAT-II: a 5-year longitudinal study. J Am Diet Assoc. Mar 2007;107(3):448–55. doi:10.1016/j.jada.2006.12.013 17324664 | Intervention/Exposure; Outcome
462 | Neve MJ, Morgan PJ, Collins CE. Behavioural factors related with successful weight loss 15 months post-enrolment in a commercial web-based weight-loss programme. Public Health Nutr. Jul 2012;15(7):1299–309. doi:10.1017/S1368980011003090 22122973 | Study design
463 | Newby PK, Weismayer C, Akesson A, Tucker KL, Wolk A. Longitudinal changes in food patterns predict changes in weight and body mass index and the effects are greatest in obese women. J Nutr. Oct 2006;136(10):2580–7. doi:10.1093/jn/136.10.2580 16988130 | Intervention/Exposure
464 | Nisselson HS. The Perils of Skipping Breakfast. J N J Dent Assoc. Fall 2015;86(4):4. | Study design
465 | Nonino-Borges CB, Martins Borges R, Bavaresco M, Suen VM, Moreira AC, Marchini JS. Influence of meal time on salivary circadian cortisol rhythms and weight loss in obese women. Nutrition. May 2007;23(5):385–91. doi:10.1016/j.nut.2007.02.007 17483007 | Intervention/Exposure; Comparator
466 | O'Brien KM, Hutchesson MJ, Jensen M, Morgan P, Callister R, Collins CE. Participants in an onlineweight loss program can improve diet quality during weight loss: a randomized controlled trial. Nutr J. Aug 9 2014;13:82. doi:10.1186/1475-2891-13-82 25108506 | Intervention/Exposure
467 | O'Connor L, Brage S, Griffin SJ, Wareham NJ, Forouhi NG. The cross-sectional association between snacking behaviour and measures of adiposity: the Fenland Study, UK. Br J Nutr. Oct 28 2015;114(8):1286–93. doi:10.1017/S000711451500269X 26343512 | Study design
468 | O'Dea JA, Wagstaff S. Increased breakfast frequency and nutritional quality among schoolchildrenafter a national breakfast promotion campaign in Australia between 2000 and 2006. Health Educ Res. Dec 2011;26(6):1086–96. doi:10.1093/her/cyr042 21685403 | Study design
469 | Ochoa-Aviles A, Verstraeten R, Huybregts L, A school-based intervention improved dietaryintake outcomes and reduced waist circumference in adolescents: a cluster randomized controlled trial. Nutr J. Dec 11 2017;16(1):79. doi:10.1186/s12937-017-0299-5 29228946 | Intervention/Exposure
470 | Oellingrath IM, Svendsen MV. BMI-specific associations between health-related behaviours and overweight - a longitudinal study among Norwegian adolescents. Public Health Nutr. Feb 2017;20(3):481–491. doi:10.1017/S1368980016002536 27652897 | Intervention/Exposure
471 | Oellingrath IM, Svendsen MV, Brantsaeter AL. Tracking of eating patterns and overweight - a follow-up study of Norwegian schoolchildren from middle childhood to early adolescence. Nutr J. Oct 6 2011;10:106. doi:10.1186/1475-2891-10-106 21978299 | Intervention/Exposure
472 | Ogata H, Hatamoto Y, Goto Y, Association between breakfast skipping and postprandial hyperglycaemia after lunch in healthy young individuals. Br J Nutr. Aug 28 2019;122(4):431–440. doi:10.1017/S0007114519001235 31486356 | Outcome
473 | Ogata H, Kayaba M, Tanaka Y, Effect of skipping breakfast for 6 days on energy metabolismand diurnal rhythm of blood glucose in young healthy Japanese males. Am J Clin Nutr. Jul 1 2019;110(1):41–52. doi:10.1093/ajcn/nqy346 31095288 | Duration
474 | Oh SY, Kim BS, Choue R. Appetite sensations and eating behaviors to complete fasting in obeseand non-obese individuals. Eur J Clin Nutr. Jan 2002;56(1):86–9. doi:10.1038/sj.ejcn.1601285 11840185 | Intervention/Exposure; Outcome
475 | Ohkawara K, Cornier MA, Kohrt WM, Melanson EL. Effects of increased meal frequency on fat oxidation and perceived hunger. Obesity (Silver Spring). Feb 2013;21(2):336–43. doi:10.1002/oby.20032 23404961 | Outcome; Duration
476 | Okubo H, Crozier SR, Harvey NC, Diet quality across early childhood and adiposity at 6 years: the Southampton Women's Survey. Int J Obes (Lond). Oct 2015;39(10):1456–62. doi:10.1038/ijo.2015.97 26121960 | Intervention/Exposure
477 | Olafsdottir AS, Skuladottir GV, Thorsdottir I, Hauksson A, Steingrimsdottir L. Maternal diet in earlyand late pregnancy in relation to weight gain. Int J Obes (Lond). Mar 2006;30(3):492–9. doi:10.1038/sj.ijo.0803184 16331301 | Intervention/Exposure
478 | Olson CM, Strawderman MS, Hinton PS, Pearson TA. Gestational weight gain and postpartum behaviorsassociated with weight change from early pregnancy to 1 y postpartum. Article. Int J Obes Relat Metab Disord. Jan 2003;27(1):117–27. doi:10.1038/sj.ijo.0802156 12532163 | Intervention/Exposure
479 | Olson J, Aldrich H, Callahan TJ, Matthews EE, Gance-Cleveland B. Characterization of ChildhoodObesity and Behavioral Factors. J Pediatr Health Care. Sep-Oct 2016;30(5):444–52. doi:10.1016/j.pedhc.2015.10.009 26614274 | Study design
480 | Orlet Fisher J, Rolls BJ, Birch LL. Children's bite size and intake of an entree are greater with large portions than with age-appropriate or self-selected portions. Am J Clin Nutr. May 2003;77(5):1164–70. doi:10.1093/ajcn/77.5.1164 12716667 | Intervention/Exposure
481 | Ovaskainen ML, Tapanainen H, Pakkala H. Changes in the contribution of snacks to the daily energy intake of Finnish adults. Appetite. Jun 2010;54(3):623–6. doi:10.1016/j.appet.2010.03.012 20347899 | Study design
482 | Özcan BA, Yeşilkay B, Yaldiz N, Pehliva M. Factors affecting diet quality in adolescents: The effectof sociodemographic characteristics and meal consumption. Article. Progress in Nutrition. 2020;22(4)doi:10.23751/pn.v22i4.10927 | Study design
483 | Pachucki MA. Food pattern analysis over time: unhealthful eating trajectories predict obesity. Int J Obes (Lond). May 2012;36(5):686–94. doi:10.1038/ijo.2011.133 21792169 | Intervention/Exposure
484 | Palmer MA, Capra S, Baines SK. Association between eating frequency, weight, and health. Nutr Rev. 2009;67(7):379–390. doi:10.1111/j.1753-4887.2009.00204.x 19566598 | Study design
485 | Papageorgiou M, Biver E, Mareschal J, The effects of time-restricted eating and weight loss on bone metabolism and health: a 6-month randomized controlled trial. Journal article. Obesity (Silver Spring). Feb 2023;31 Suppl 1(Suppl 1):85–95. doi:10.1002/oby.23577 36239695 | Intervention/Exposure
486 | Papakonstantinou E, Kechribari I, Mitrou P, Effect of meal frequency on glucose and insulin levels in women with polycystic ovary syndrome: a randomised trial. Eur J Clin Nutr. May 2016;70(5):588–94. doi:10.1038/ejcn.2015.225 26862008 | Health status
487 | Park SJ, Yang JW, Song YJ. The Effect of Four Weeks Dietary Intervention with 8-Hour Time-Restricted Eating on Body Composition and Cardiometabolic Risk Factors in Young Adults. Nutrients. Jun 24 2021;13(7):2164–2164. doi:10.3390/nu13072164 34202475 | Intervention/Exposure
488 | Park SY, Shvetsov YB, Kang M, Changes in Diet Quality over 10 Years Are Associated with Baseline Sociodemographic and Lifestyle Factors in the Multiethnic Cohort Study. J Nutr. Jul 1 2020;150(7):1880–1888. doi:10.1093/jn/nxaa102 32338763 | Study design; Intervention/Exposure
489 | Parkes KR. Demographic and lifestyle predictors of body mass index among offshore oil industryworkers: cross-sectional and longitudinal findings. Occup Med (Lond). May 2003;53(3):213–21. doi:10.1093/occmed/kqg037 12724556 | Intervention/Exposure
490 | Parr EB, Devlin BL, Hawley JA. Perspective: Time-Restricted Eating-Integrating the What with the When. Adv Nutr. Jun 1 2022;13(3):699–711. doi:10.1093/advances/nmac015 35170718 | Study design; Intervention/Exposure
491 | Parr EB, Devlin BL, Radford BE, Hawley JA. A Delayed Morning and Earlier Evening Time-Restricted Feeding Protocol for Improving Glycemic Control and Dietary Adherence in Men with Overweight/Obesity: A Randomized Controlled Trial. Journal article. Nutrients. Feb 17 2020;12(2)doi:10.3390/nu12020505 | Intervention/Exposure; Comparator
492 | Parr EB, Dunstan DW, Pinto SK, Leckey JJ, Hawley JA. Effects of a large breakfast versus large dinner on 24-h blood glucose profiles during a day of prolonged sedentary behaviour. Obesity Research & Clinical Practice. 2019;13(1):36–36. doi:10.1016/j.orcp.2016.10.043 | Intervention/Exposure
493 | Parr EB, Kouw IWK, Wheeler MJ, Eight-hour time-restricted eating does not lower daily myofibrillar protein synthesis rates: A randomized control trial. Obesity (Silver Spring). Feb 2023;31 Suppl 1(Suppl 1):116–126. doi:10.1002/oby.23637 36546330 | Intervention/Exposure; Publication status
494 | Patrick K, Raab F, Adams MA, A text message-based intervention for weight loss: randomized controlled trial. J Med Internet Res. Jan 13 2009;11(1):e1. doi:10.2196/jmir.1100 19141433 | Intervention/Exposure
495 | Patterson KAE, Ferrar K, Gall SL, Cluster patterns of behavioural risk factors among children: Longitudinal associations with adult cardio-metabolic risk factors. Prev Med. Jan 2020;130:105861. doi:10.1016/j.ypmed.2019.105861 31654729 | Intervention/Exposure
496 | Pearson N, Griffiths P, Biddle SJH, Johnston JP, Haycraft E. Individual, behavioural and home environmentalfactors associated with eating behaviours in young adolescents. Appetite. May 1 2017;112:35–43. doi:10.1016/j.appet.2017.01.001 28062200 | Study design
497 | Peeke PM, Greenway FL, Billes SK, Zhang D, Fujioka K. Effect of time restricted eating on body weight and fasting glucose in participants with obesity: results of a randomized, controlled, virtual clinical trial. Nutr Diabetes. Jan 15 2021;11(1):6. doi:10.1038/s41387-021-00149-0 33446635 | Intervention/Exposure; Comparator
498 | Peh EWY, Koecher K, Menon R, Henry CJ. Breakfast consumption modulates postprandial glycaemic, insulinaemic and NEFA response in pre-diabetic Asian males. Br J Nutr. Mar 28 2020;123(6):664–672. doi:10.1017/S0007114519003180 31831088 | Outcome
499 | Peneau S, Thibault H, Meless D, Anthropometric and behavioral patterns associated with weightmaintenance after an obesity treatment in adolescents. J Pediatr. May 2008;152(5):678–84. doi:10.1016/j.jpeds.2007.09.053 | Study design; Intervention/Exposure
500 | Peplonska B, Kaluzny P, Trafalska E. Rotating night shift work and nutrition of nurses and midwives. Chronobiol Int. Jul 2019;36(7):945–954. doi:10.1080/07420528.2019.1602051 31056960 | Study design
501 | Pereira MA, Erickson E, McKee P, Breakfast frequency and quality may affect glycemia andappetite in adults and children. J Nutr. Jan 2011;141(1):163–8. doi:10.3945/jn.109.114405 21123469 | Study design; Outcome
502 | Perrigue MM, Drewnowski A, Ching-Yun W, Neuhouser ML, Wang C-Y. Higher Eating Frequency Does Not Decrease Appetite in Healthy Adults. J Nutr. 2016;146(1):59–64. doi:10.3945/jn.115.216978 26561409 | Outcome
503 | Perrigue MM, Drewnowski A, Wang CY, Song X, Kratz M, Neuhouser ML. Randomized Trial Testingthe Effects of Eating Frequency on Two Hormonal Biomarkers of Metabolism and Energy Balance. Nutr Cancer. Jan 2017;69(1):56–63. doi:10.1080/01635581.2017.1247888 27918854 | Duration
504 | Phelan S, Wyatt H, Nassery S, Three-year weight change in successful weight losers who lostweight on a low-carbohydrate diet. Obesity (Silver Spring). Oct 2007;15(10):2470–7. doi:10.1038/oby.2007.293 17925473 | Intervention/Exposure
505 | Pineda Vargas SS, O'Neil CE, Keast DR, Cho SS, Nicklas TA. Eating Ready-to-Eat Cereal for Breakfast is Positively Associated With Daily Nutrient Intake, but Not Weight, in Mexican-American Children and Adolescents. Nutrition Today. 2016;51(4):206–215. doi:10.1097/NT.0b013e3182993988 | Study design; Intervention/Exposure; Comparator
506 | Pinto AM, Bordoli C, Buckner LP, Intermittent energy restriction is comparable to continuous energy restriction for cardiometabolic health in adults with central obesity: a randomized controlled trial; the Met-IER study. Journal Article; Clinical Trial Protocol. Clin Nutr. 2020;39(6):1753‐1763. doi:10.1016/j.clnu.2019.07.014 31409509 | Intervention/Exposure
507 | Pizinger T, Kovtun K, RoyChoudhury A, Laferrere B, Shechter A, St-Onge MP. Pilot study of sleepand meal timing effects, independent of sleep duration and food intake, on insulin sensitivityin healthy individuals. Sleep Health. Feb 2018;4(1):33–39. doi:10.1016/j.sleh.2017.10.005 29332677 | Intervention/Exposure
508 | Polonsky HM, Bauer KW, Fisher JO, Effect of a Breakfast in the Classroom Initiative on Obesityin Urban School-aged Children: A Cluster Randomized Clinical Trial. JAMA Pediatr. Apr 1 2019;173(4):326–333. doi:10.1001/jamapediatrics.2018.5531 30801612 | Intervention/Exposure
509 | Pot GK, Hardy R, Stephen AM. Irregularity of energy intake at meals: prospective associations with the metabolic syndrome in adults of the 1946 British birth cohort. Br J Nutr. Jan 28 2016;115(2):315–23. doi:10.1017/S0007114515004407 26548599 | Intervention/Exposure
510 | Pouliot C, Biagé A, Prud'homme D, Giroux I. Effect of weight status on dietary response to an 8-week aerobic exercise program in previously inactive adolescents. Article. Obesity Medicine. 2021;25doi:10.1016/j.obmed.2021.100363 | Intervention/Exposure
511 | Power TG, Hidalgo-Mendez J, Fisher JO, O'Connor TM, Micheli N, Hughes SO. Obesity risk in Hispanicchildren: Bidirectional associations between child eating behavior and child weight status over time. Eat Behav. Jan 2020;36:101366. doi:10.1016/j.eatbeh.2020.101366 31962209 | Intervention/Exposure
512 | Prasad M, Fine K, Gee A, A Smartphone Intervention to Promote Time Restricted Eating ReducesBody Weight and Blood Pressure in Adults with Overweight and Obesity: A Pilot Study. Nutrients. Jun 23 2021;13(7)doi:10.3390/nu13072148 | Study design; Intervention/Exposure
513 | Purslow LR, Sandhu MS, Forouhi N, Energy intake at breakfast and weight change: prospective study of 6,764 middle-aged men and women. Am J Epidemiol. Jan 15 2008;167(2):188–92. doi:10.1093/aje/kwm309 18079134 | Study design; Intervention/Exposure; Other
514 | Queiroz JDN, Macedo RCO, Dos Santos GC, Cardiometabolic effects of early v. delayed time-restricted eating plus energetic restriction in adults with overweight and obesity: an exploratory randomised clinical trial. Br J Nutr. May 26 2022:1–13. doi:10.1017/S0007114522001581 | Intervention/Exposure; Comparator
515 | Queiroz JDN, Macedo RCO, Dos Santos GC, Cardiometabolic Effects of Early vs. Delayed Time-Restricted Eating Plus Caloric Restriction in Adults with Overweight and Obesity: an Exploratory Randomized Clinical Trial. Journal article. Br J Nutr. 2022:1‐36. doi:10.1017/S0007114522001581 | Intervention/Exposure; Comparator
516 | Racette SB, Deusinger SS, Strube MJ, Highstein GR, Deusinger RH. Weight changes, exercise, and dietary patterns during freshman and sophomore years of college. J Am Coll Health. May-Jun 2005;53(6):245–51. doi:10.3200/JACH.53.6.245-251 15900988 | Intervention/Exposure
517 | Racz B, Duskova M, Starka L, Hainer V, Kunesova M. Links between the circadian rhythm, obesity and the microbiome. Physiol Res. Nov 28 2018;67(Suppl 3):S409–S420. doi:10.33549/physiolres.934020 30484668 | Study design
518 | Rafique N. Body mass index, eating habits, and various lifestyle changes in young adults duringthe two years of the coronavirus disease 2019 (COVID-19) pandemic. J Family Community Med. Sep-Dec 2022;29(3):189–195. doi:10.4103/jfcm.jfcm_74_22 36389028 | Study design
519 | Rampersaud GC, Pereira MA, Girard BL, Adams J, Metzl JD. Breakfast habits, nutritional status, body weight, and academic performance in children and adolescents. J Am Diet Assoc. May 2005;105(5):743–60; quiz 761–2. doi:10.1016/j.jada.2005.02.007 15883552 | Study design
520 | Rashidi MR, Mahboob S, Sattarivand R. Effects of nibbling and gorging on lipid profiles, blood glucose and insulin levels in healthy subjects. Saudi Med J. Sep 2003;24(9):945–8.12973474 | Intervention/Exposure; Outcome
521 | Rashidi MR, Rahnama B. Effect of meal frequency on human serum complements C3 and C4. Article. Iranian Journal of Basic Medical Sciences. 2008;11(1):49–54. doi:10.22038/IJBMS.2008.5196 | Outcome
522 | Ray C, Roos E. Family characteristics predicting favourable changes in 10 and 11-year-old children's lifestyle-related health behaviours during an 18-month follow-up. Appetite. Feb 2012;58(1):326–32. doi:10.1016/j.appet.2011.10.009 22056489 | Intervention/Exposure; Outcome
523 | Raynor HA, Li F, Cardoso C. Daily pattern of energy distribution and weight loss. Physiol Behav. Aug 1 2018;192:167–172. doi:10.1016/j.physbeh.2018.02.036 29471076 | Comparator; Duration
524 | Raynor HA, Niemeier HM, Wing RR. Effect of limiting snack food variety on long-term sensory-specific satiety and monotony during obesity treatment. Eat Behav. Jan 2006;7(1):1–14. doi:10.1016/j.eatbeh.2005.05.005 16360618 | Intervention/Exposure; Comparator
525 | Raynor HA, Thomas JG, Cardoso CC, Wojtanowski AC, Foster GD. Examining the pattern of new foods and beverages consumed during obesity treatment to inform strategies for self-monitoring intake. Appetite. Jan 1 2019;132:147–153. doi:10.1016/j.appet.2018.10.018 30326244 | Intervention/Exposure
526 | Reeves S, Huber JW, Halsey LG, Villegas-Montes M, Elgumati J, Smith T. A cross-over experiment to investigate possible mechanisms for lower BMIs in people who habitually eat breakfast. Eur J Clin Nutr. May 2015;69(5):632–7. doi:10.1038/ejcn.2014.269 25563734 | Outcome
527 | Reicks M, Davey C, Anderson AK, P24 - Frequency of Eating Alone Among Adolescents wasAssociated with Parent Support, Dietary Intake and BMI: FLASHE Study Results. J Nutr Educ Behav. 2018;50:S19–S19. doi:10.1016/j.jneb.2018.04.053 | Study design; Publication status
528 | Reid KJ, Baron KG, Zee PC. Meal timing influences daily caloric intake in healthy adults. Nutr Res. Nov 2014;34(11):930–5. doi:10.1016/j.nutres.2014.09.010 25439026 | Study design
529 | Renault KM, Carlsen EM, Norgaard K, Intake of Sweets, Snacks and Soft Drinks Predicts Weight Gain in Obese Pregnant Women: Detailed Analysis of the Results of a Randomised ControlledTrial. PLoS One. 2015;10(7):e0133041. doi:10.1371/journal.pone.0133041 26192183 | Intervention/Exposure
530 | Richardson CE, Tovar AP, Davis BA, Van Loan MD, Keim NL, Casazza GA. An Intervention of Four Weeks of Time-Restricted Eating (16/8) in Male Long-Distance Runners Does Not Affect CardiometabolicRisk Factors. Nutrients. Feb 16 2023;15(4)doi:10.3390/nu15040985 | Intervention/Exposure
531 | Rito AI, Dinis A, Rascoa C, Improving breakfast patterns of portuguese children-an evaluationof ready-to-eat cereals according to the European nutrient profile model. Eur J Clin Nutr. Mar 2019;73(3):465–473. doi:10.1038/s41430-018-0235-6 29973677 | Outcome
532 | Roberge JB, Van Hulst A, Barnett TA, Lifestyle Habits, Dietary Factors, and the MetabolicallyUnhealthy Obese Phenotype in Youth. J Pediatr. Jan 2019;204:46–52 e1. doi:10.1016/j.jpeds.2018.08.063 | Intervention/Exposure
533 | Robinson WR, Stevens J, Kaufman JS, Gordon-Larsen P. The role of adolescent behaviors in thefemale-male disparity in obesity incidence in US black and white young adults. Obesity (Silver Spring). Jul 2010;18(7):1429–36. doi:10.1038/oby.2009.362 19875993 | Intervention/Exposure
534 | Rollins BY, Loken E, Birch LL. Preferences predict food intake from 5 to 11 years, but not in girls with higher weight concerns, dietary restraint, and %body fat. Obesity (Silver Spring). Nov 2011;19(11):2190–7. doi:10.1038/oby.2011.28 21350438 | Intervention/Exposure
535 | Rooney BL, Mathiason MA, Schauberger CW. Predictors of obesity in childhood, adolescence, and adulthood in a birth cohort. Matern Child Health J. Nov 2011;15(8):1166–75. doi:10.1007/s10995-010-0689-1 20927643 | Intervention/Exposure
536 | Rosenrauch S, Ball K, Lamb KE. Associations between perceived friends' support of healthy eatingand meal skipping in adolescence. Public Health Nutr. Dec 2017;20(18):3266–3274. doi:10.1017/S136898001700235X 28879821 | Intervention/Exposure; Outcome
537 | Ross KM, Qiu P, You L, Wing RR. Week-to-week predictors of weight loss and regain. Health Psychol. Dec 2019;38(12):1150–1158. doi:10.1037/hea0000798 31566400 | Intervention/Exposure
538 | Rossbach S, Diederichs T, Bolzenius K, Herder C, Buyken AE, Alexy U. Age and time trends in eating frequency and duration of nightly fasting of German children and adolescents. Eur J Nutr. Dec 2017;56(8):2507–2517. doi:10.1007/s00394-016-1286-x 27492443 | Outcome
539 | Ruddick-Collins LC, Morgan PJ, Fyfe CL, Timing of daily calorie loading affects appetite and hunger responses without changes in energy metabolism in healthy subjects with obesity. Cell Metab. Oct 4 2022;34(10):1472–1485 e6. doi:10.1016/j.cmet.2022.08.001 36087576 | Intervention/Exposure; Comparator
540 | Saals B, Boss HM, Pot GK. Young people and adolescents have more irregular meals during the COVID-19 pandemic: A nested case-control study on chrono-nutrition before and during the COVID-19 pandemic. Chronobiol Int. Jul 2022;39(7):991–1000. doi:10.1080/07420528.2022.2054347 35354418 | Intervention/Exposure; Outcome
541 | Saarilehto S, Lapinleimu H, Keskinen S, Helenius H, Talvia S, Simell O. Growth, energy intake, and meal pattern in five-year-old children considered as poor eaters. J Pediatr. Mar 2004;144(3):363–7. doi:10.1016/j.jpeds.2003.12.028 | Study design; Intervention/Exposure
542 | Saini SK, Singh A, Saini M, Gonzalez-Freire M, Leeuwenburgh C, Anton SD. Time-Restricted EatingRegimen Differentially Affects Circulatory miRNA Expression in Older Overweight Adults. Nutrients. Apr 28 2022;14(9)doi:10.3390/nu14091843 | Intervention/Exposure
543 | Saldanha-Gomes C, Marbac M, Sedki M, Clusters of diet, physical activity, television exposure and sleep habits and their association with adiposity in preschool children: the EDEN mother-child cohort. Int J Behav Nutr Phys Act. 2020;17(1):1–13. doi:10.1186/s12966-020-00927-6 31898547 | Intervention/Exposure
544 | Salunkhe AH, Pratinidhi A, Salunkhe JA, Kakade SV, Mohite VR, Hiremath P. Frequency and Nutrient Content of Meals of the Mothers and the Birth Weight and Gestational Age of the Baby. Article. Journal of Krishna Institute of Medical Sciences University. Apr-Jun 2018;7(2):33– 41. | Outcome; Country
545 | Sánchez-Villegas A, Martínez-González MÁ, Toledo E, Relative role of physical inactivity and snacking between meals in weight gain. Article. Medicina Clinica. 2002;119(2):46–52. doi:10.1016/s0025-7753(02)73311-3 12084369 | Study design; Language
546 | Sandvik P, Kuronen S, Reijs Richards H, Associations of preschoolers' dietary patterns witheating behaviors and parental feeding practices at a 12-month follow-up of obesity treatment. Appetite. Jan 1 2022;168:105724. doi:10.1016/j.appet.2021.105724 34606942 | Intervention/Exposure
547 | Santonja I, Bogl LH, Degenfellner J, Meal-timing patterns and chronic disease prevalence intwo representative Austrian studies. Eur J Nutr. Jun 2023;62(4):1879–1890. doi:10.1007/s00394-023-03113-z 36864319 | Study design
548 | Sari DK. Impact of breakfast counselling and 6 days of breakfast on the nutritional status and knowledge of middle school students in berastagi, indonesia. Article. Pakistan Journal of Nutrition. 2019;19(1):12–18. doi:10.3923/pjn.2020.12.18 | Study design; Outcome
549 | Sartorelli DS, Franco LJ, Cardoso MA. High intake of fruits and vegetables predicts weight loss inBrazilian overweight adults. Nutr Res. Apr 2008;28(4):233–8. doi:10.1016/j.nutres.2008.02.004 19083413 | Intervention/Exposure
550 | Sata M, Yamagishi K, Sairenchi T, Impact of Caregiver Type for 3-Year-Old Children on Subsequent Between-Meal Eating Habits and Being Overweight From Childhood to Adulthood: A 20-Year Follow-up of the Ibaraki Children's Cohort (IBACHIL) Study. J Epidemiol. 2015;25(9):600–7. doi:10.2188/jea.JE20140078 26310570 | Intervention/Exposure
551 | Sata M, Yamagishi K, Sairenchi T, Long-term effect of feeding snacks at age 6 years on bodymass index at ages 12 and 22 years. Sci Rep. Jun 13 2019;9(1):8627. doi:10.1038/s41598-019-40730-3 31197204 | Intervention/Exposure
552 | Savage JS, Birch LL. Patterns of weight control strategies predict differences in women's 4-year weight gain. Obesity (Silver Spring). Mar 2010;18(3):513–20. doi:10.1038/oby.2009.265 19696759 | Intervention/Exposure; Outcome
553 | Savage JS, Hoffman L, Birch LL. Dieting, restraint, and disinhibition predict women's weight change over 6 y. Am J Clin Nutr. Jul 2009;90(1):33–40. doi:10.3945/ajcn.2008.26558 19439461 | Intervention/Exposure
554 | Scholtens S, Brunekreef B, Smit HA, Do differences in childhood diet explain the reduced overweight risk in breastfed children? Obesity (Silver Spring). Nov 2008;16(11):2498–503. doi:10.1038/oby.2008.403 18756263 | Intervention/Exposure
555 | Schusdziarra V, Hausmann M, Wiedemann C, Successful weight loss and maintenance in everyday clinical practice with an individually tailored change of eating habits on the basis of foodenergy density. Eur J Nutr. Aug 2011;50(5):351–61. doi:10.1007/s00394-010-0143-6 21120658 | Intervention/Exposure
556 | Schusdziarra V, Hausmann M, Wittke C, Contribution of energy density and food quantity toshort-term fluctuations of energy intake in normal weight and obese subjects. Eur J Nutr. Feb 2010;49(1):37–43. doi:10.1007/s00394-009-0046-6 19669825 | Study design
557 | Schwedhelm C, Lipsky LM, Temmen CD, Nansel TR. Eating Patterns during Pregnancy and Postpartumand Their Association with Diet Quality and Energy Intake. Nutrients. Mar 10 2022;14(6)doi:10.3390/nu14061167 | Study design
558 | Schwingel A, Nakata Y, Ito LS, Central obesity and health-related factors among middle-aged men: a comparison among native Japanese and Japanese-Brazilians residing in Brazil andJapan. J Physiol Anthropol. May 2007;26(3):339–47. doi:10.2114/jpa2.26.339 17641453 | Intervention/Exposure
559 | Sedibe MH, Pisa PT, Feeley AB, Pedro TM, Kahn K, Norris SA. Dietary Habits and Eating Practices and Their Association with Overweight and Obesity in Rural and Urban Black South AfricanAdolescents. Nutrients. Jan 29 2018;10(2)doi:10.3390/nu10020145 | Study design; Country
560 | Sen B. Frequency of family dinner and adolescent body weight status: evidence from the national longitudinal survey of youth, 1997. Obesity (Silver Spring). Dec 2006;14(12):2266–76. doi:10.1038/oby.2006.266 17189555 | Intervention/Exposure
561 | Shahar DR, Schultz R, Shahar A, Wing RR. The effect of widowhood on weight change, dietary intake, and eating behavior in the elderly population. J Aging Health. May 2001;13(2):189–99. doi:10.1177/089826430101300202 11787511 | Study design; Intervention/Exposure
562 | Shatenstein B, Nadon S, Ferland G. Determinants of diet quality among Quebecers aged 55–74. J Nutr Health Aging. 2004;8(2):83–91.14978603 | Study design; Outcome
563 | Shaw E, Dorrian J, Coates AM, Temporal pattern of eating in night shift workers. Chronobiol Int. Dec 2019;36(12):1613–1625. doi:10.1080/07420528.2019.1660358 31495232 | Study design; Intervention/Exposure
564 | Shriver L, Marriage B, Bloch T, Spees C, Ramsay S, Taylor C. Snacking Behaviors among Young Children: Examination of Snacking Across Racial/Ethnic Groups in the U.S. J Acad Nutr Diet. 2016;116:A31–A31. doi:10.1016/j.jand.2016.06.105 | Publication status
565 | Siahpush M, Tibbits M, Shaikh RA, Singh GK, Sikora Kessler A, Huang TT. Dieting Increases the Likelihood of Subsequent Obesity and BMI Gain: Results from a Prospective Study of an Australian National Sample. Int J Behav Med. Oct 2015;22(5):662–71. doi:10.1007/s12529-015-9463-5 25608460 | Intervention/Exposure
566 | Siedler MR, Lewis MH, Trexler ET, The Effects of Intermittent Diet Breaks during 25% Energy Restriction on Body Composition and Resting Metabolic Rate in Resistance-Trained Females: A Randomized Controlled Trial. J Hum Kinet. Mar 2023;86:117–132. doi:10.5114/jhk/159960 37181269 | Intervention/Exposure
567 | Siega-Riz AM, Herrmann TS, Savitz DA, Thorp JM. Frequency of eating during pregnancy and itseffect on preterm delivery. Am J Epidemiol. Apr 1 2001;153(7):647–52. doi:10.1093/aje/153.7.647 11282791 | Study design; Outcome
568 | Sila S, Ilic A, Misigoj-Durakovic M, Soric M, Radman I, Satalic Z. Obesity in Adolescents Who SkipBreakfast Is Not Associated with Physical Activity. Nutrients. Oct 18 2019;11(10)doi:10.3390/nu11102511 | Study design
569 | Simon SL, Blankenship J, Manoogian ENC, Panda S, Mashek DG, Chow LS. The impact of a self-selected time restricted eating intervention on eating patterns, sleep, and late-night eating inindividuals with obesity. Front Nutr. 2022;9:1007824. doi:10.3389/fnut.2022.1007824 36337640 | Intervention/Exposure
570 | Simon SL, Pan Z, Marden T, Body mass index and variability in meal duration and association with rate of eating. Front Nutr. 2022;9:941001. doi:10.3389/fnut.2022.941001 35958246 | Study design; Intervention/Exposure
571 | Singh RB, Cornelissen G, Mojto V, Effects of circadian restricted feeding on parameters of metabolicsyndrome among healthy subjects. Journal article. Chronobiol Int. 2020;37(3):395‐ 402. doi:10.1080/07420528.2019.1701817 31847602 | Intervention/Exposure; Comparator
572 | Sitzman K. Eating breakfast helps sustain weight loss. AAOHN Journal. 2006;54(3):136–136. doi:10.1177/216507990605400307 16562625 | Study design
573 | Skinner JD, Ziegler P, Pac S, Devaney B. Meal and snack patterns of infants and toddlers. J Am Diet Assoc. Jan 2004;104(1 Suppl 1):s65–70. doi:10.1016/j.jada.2003.10.021 14702020 | Study design
574 | Skoczek-Rubinska A, Muzsik-Kazimierska A, Chmurzynska A, Walkowiak PJ, Bajerska J. Snacking may improve dietary fiber density and is associated with a lower body mass index in postmenopausal women. Nutrition. Mar 2021;83:111063. doi:10.1016/j.nut.2020.111063 33352354 | Study design
575 | Slomski A. Adding Time-Restricted Eating to Caloric Restriction for Weight Loss. JAMA. May 24 2022;327(20):1950. doi:10.1001/jama.2022.8018 | Study design
576 | Smeets AJ, Westerterp-Plantenga MS. Acute effects on metabolism and appetite profile of one meal difference in the lower range of meal frequency. Br J Nutr. Jun 2008;99(6):1316–21. doi:10.1017/S0007114507877646 18053311 | Outcome
577 | Smith KJ, McNaughton SA, Gall SL, Otahal P, Dwyer T, Venn AJ. Associations between Partneringand Parenting Transitions and Dietary Habits in Young Adults. J Acad Nutr Diet. Aug 2017;117(8):1210–1221. doi:10.1016/j.jand.2016.12.008 28169212 | Intervention/Exposure
578 | Soini S, Mustajoki P, Eriksson JG. Weight loss methods and changes in eating habits among successful weight losers. Ann Med. 2016;48(1–2):76–82. doi:10.3109/07853890.2015.1136428 26820173 | Study design; Outcome
579 | Solomon TP, Chambers ES, Jeukendrup AE, Toogood AA, Blannin AK. The effect of feeding frequencyon insulin and ghrelin responses in human subjects. Br J Nutr. Oct 2008;100(4):810–9. doi:10.1017/S000711450896757X 18394217 | Outcome
580 | Soreca I, Wallace ML, Hall MH, Hasler BP, Frank E, Kupfer DJ. The association between meal timingand frequency with cardiometabolic profile in patients with bipolar disorder. Acta Psychiatr Scand. Jun 2016;133(6):453–8. doi:10.1111/acps.12578 27084394 | Study design; Intervention/Exposure
581 | St-Onge MP, Pizinger T, Kovtun K, RoyChoudhury A. Sleep and meal timing influence food intake and its hormonal regulation in healthy adults with overweight/obesity. Eur J Clin Nutr. Jul 2019;72(Suppl 1):76–82. doi:10.1038/s41430-018-0312-x 30487565 | Intervention/Exposure
582 | Steger FL, Jamshed H, Bryan DR, Early time-restricted eating affects weight, metabolic health, mood, and sleep in adherent completers: A secondary analysis. Obesity (Silver Spring). Feb 2023;31 Suppl 1(Suppl 1):96–107. doi:10.1002/oby.23614 | Intervention/Exposure
583 | Steger FL, Jamshed H, Martin CK, Impact of early time-restricted eating on diet quality, meal frequency, appetite, and eating behaviors: A randomized trial. Obesity (Silver Spring). Feb 2023;31 Suppl 1(Suppl 1):127–138. doi:10.1002/oby.23642 36575143 | Intervention/Exposure
584 | Stennett M, Blokland A, Watt RG, Heilmann A. Mid-adolescent ethnic variations in overweight prevalencein the UK Millennium Cohort Study. Eur J Public Health. Apr 24 2021;31(2):396–402. doi:10.1093/eurpub/ckab023 33895848 | Study design; Intervention/Exposure
585 | Stockman NK, Schenkel TC, Brown JN, Duncan AM. Comparison of energy and nutrient intakesamong meals and snacks of adolescent males. Prev Med. Jul 2005;41(1):203–10. doi:10.1016/j.ypmed.2004.11.001 15917012 | Study design
586 | Stote KS, Baer DJ, Spears K, A controlled trial of reduced meal frequency without caloric restriction in healthy, normal-weight, middle-aged adults. Journal article. Am J Clin Nutr. 2007;85(4):981‐988. doi:10.1093/ajcn/85.4.981 17413096 | Intervention/Exposure; Duration
587 | Stratton MT, Tinsley GM, Alesi MG, Four weeks of time-restricted feeding combined with resistance training does not differentially influence measures of body composition, muscle performance, resting energy expenditure, and blood biomarkers. Journal article. Nutrients. 2020;12(4)doi:10.3390/nu12041126 | Intervention/Exposure
588 | Strojny Z, Rutkowski R, Kanikowska A, No Significant Effect of the Individual Chronotype onthe Result of Moderate Calorie Restriction for Obesity-A Pilot Study. Nutrients. Nov 15 2021;13(11)doi:10.3390/nu13114089 | Intervention/Exposure; Comparator
589 | Stubbs J, Brogelli D, Pallister C, Avery A, McConnon A, Lavin J. Behavioural and motivational factorsassociated with weight loss and maintenance in a commercial weight management programme. Article. Open Obesity Journal. 2012;4:35–43. doi:10.2174/1876823701204010035 | Study design
590 | Stunkard AJ, Berkowitz RI, Schoeller D, Maislin G, Stallings VA. Predictors of body size in the first2 y of life: a high-risk study of human obesity. Int J Obes Relat Metab Disord. Apr 2004;28(4):503–13. doi:10.1038/sj.ijo.0802517 14758342 | Population Life Stage; Intervention/Exposure
591 | Sudharsanan N, Romano S, Cunningham SA. School Breakfast Receipt and Obesity among American Fifth- and Eighth-Graders. J Acad Nutr Diet. Apr 2016;116(4):599–607 e3. doi:10.1016/j.jand.2015.08.021 27046061 | Intervention/Exposure
592 | Sugimori H, Yoshida K, Izuno T, Analysis of factors that influence body mass index from ages3 to 6 years: A study based on the Toyama cohort study. Pediatr Int. Jun 2004;46(3):302–10. doi:10.1111/j.1442-200x.2004.01895.x 15151547 | Study design
593 | Sugiura T, Dohi Y, Takagi Y, Impacts of lifestyle behavior and shift work on visceral fat accumulationand the presence of atherosclerosis in middle-aged male workers. Hypertens Res. Mar 2020;43(3):235–245. doi:10.1038/s41440-019-0362-z 31780790 | Study design
594 | Sugiyama S, Okuda M, Sasaki S, Kunitsugu I, Hobara T. Breakfast habits among adolescents and their association with daily energy and fish, vegetable, and fruit intake: a community-based cross-sectional study. Environ Health Prev Med. Sep 2012;17(5):408–14. doi:10.1007/s12199-012-0270-1 22351508 | Study design
595 | Sutton EF, Beyl R, Early KS, Cefalu WT, Ravussin E, Peterson CM. Early Time-Restricted Feeding Improves Insulin Sensitivity, Blood Pressure, and Oxidative Stress Even without WeightLoss in Men with Prediabetes. Cell Metab. Jun 5 2018;27(6):1212–1221 e3. doi:10.1016/j.cmet.2018.04.010 29754952 | Intervention/Exposure; Comparator
596 | Svensson M, Hult M, van der Mark M, The change in eating behaviors in a Web-based weight loss program: a longitudinal analysis of study completers. J Med Internet Res. Nov 3 2014;16(11):e234. doi:10.2196/jmir.3131 25367316 | Intervention/Exposure
597 | Szpak A, Jamiolkowski J, Witana K. Overweight and obesity and their determinants among menfrom Podlasie region in the years 1987–1998. Rocz Akad Med Bialymst. 2005;50 Suppl 1:245–9.16119678 | Intervention/Exposure
598 | Taguchi M, Hara A, Murata H, Torii S, Sako T. Increasing Meal Frequency in Isoenergetic Conditions Does Not Affect Body Composition Change and Appetite During Weight Gain in JapaneseAthletes. Int J Sport Nutr Exerc Metab. Mar 1 2021;31(2):109–114. doi:10.1123/ijsnem.2020-0139 33361498 | Outcome; Duration
599 | Taillie LS, Afeiche MC, Eldridge AL, Popkin BM. Increased Snacking and Eating Occasions Are Associatedwith Higher Energy Intake among Mexican Children Aged 2–13 Years. J Nutr. Nov 2015;145(11):2570–7. doi:10.3945/jn.115.213165 26377759 | Country
600 | Taillie LS, Dantong W, Popkin BM, Wang D. Snacking Is Longitudinally Associated with Declinesin Body Mass Index z Scores for Overweight Children, but Increases for Underweight Children. J Nutr. 2016;146(6):1268–1275. doi:10.3945/jn.115.226803 27146917 | Study design
601 | Tajima M, Lee JS, Watanabe E, Association between changes in 12 lifestyle behaviors and the development of metabolic syndrome during 1 year among workers in the Tokyo metropolitanarea. Circ J. 2014;78(5):1152–9. doi:10.1253/circj.cj-13-1082 24583972 | Outcome
602 | Tang J, Dong JY, Eshak ES, Supper Timing and Cardiovascular Mortality: The Japan Collaborative Cohort Study. Nutrients. Sep 27 2021;13(10)doi:10.3390/nu13103389 | Intervention/Exposure; Outcome
603 | Tang X, Andres A, West DS, Lou X, Krukowski RA. Eating behavior and weight gain during pregnancy. Eat Behav. Jan 2020;36:101364. doi:10.1016/j.eatbeh.2020.101364 32032810 | Intervention/Exposure
604 | Tani Y, Asakura K, Sasaki S, Higher proportion of total and fat energy intake during the morningmay reduce absolute intake of energy within the day. An observational study in free-living Japanese adults. Appetite. Sep 2015;92:66–73. doi:10.1016/j.appet.2015.04.071 25937510 | Study design; Intervention/Exposure
605 | Tanofsky-Kraff M, Cohen ML, Yanovski SZ, A prospective study of psychological predictorsof body fat gain among children at high risk for adult obesity. Pediatrics. Apr 2006;117(4):1203–9. doi:10.1542/peds.2005-1329 | Intervention/Exposure
606 | Tatone-Tokuda F, Dubois L, Ramsay T, Sex differences in the association between sleep duration, diet and body mass index: a birth cohort study. J Sleep Res. Aug 2012;21(4):448–60. doi:10.1111/j.1365-2869.2011.00989.x 22151014 | Intervention/Exposure; Outcome
607 | Taveras EM, Rifas-Shiman SL, Berkey CS, Family dinner and adolescent overweight. Obes Res. May 2005;13(5):900–6. doi:10.1038/oby.2005.104 15919844 | Intervention/Exposure
608 | Teo R, Pink AE, Cheon BK. Snack intake mediates the relationship between social exclusion and body mass index. Appetite. 2022;169:N.PAG-N.PAG. doi:10.1016/j.appet.2021.105565 | Publication status
609 | Teong XT, Liu K, Vincent AD, Intermittent fasting plus early time-restricted eating versus calorie restriction and standard care in adults at risk of type 2 diabetes: a randomized controlled trial. Journal article; Clinical trial protocol. Nature Medicine. 2023;29(4):963‐972. doi:10.1038/s41591-023-02287-7 | Intervention/Exposure
610 | Thomas EA, Zaman A, Cornier MA, Later Meal and Sleep Timing Predicts Higher Percent Body Fat. Nutrients. Dec 29 2020;13(1)doi:10.3390/nu13010073 | Intervention/Exposure
611 | Thomas EA, Zaman A, Sloggett KJ, Early time-restricted eating compared with daily caloricrestriction: A randomized trial in adults with obesity. Article. Obesity (Silver Spring). May 2022;30(5):1027–1038. doi:10.1002/oby.23420 35470974 | Intervention/Exposure
612 | Thomas JG, Bond DS, Phelan S, Hill JO, Wing RR. Weight-loss maintenance for 10 years in the National Weight Control Registry. Am J Prev Med. Jan 2014;46(1):17–23. doi:10.1016/j.amepre.2013.08.019 24355667 | Intervention/Exposure
613 | Thompson OM, Ballew C, Resnicow K, Food purchased away from home as a predictor of changein BMI z-score among girls. Int J Obes Relat Metab Disord. Feb 2004;28(2):282–9. doi:10.1038/sj.ijo.0802538 14647177 | Intervention/Exposure
614 | Timko CA, Mooney K, Juarascio A. Change in eating and body related behaviors during the firstyear of university. Eat Weight Disord. Mar-Jun 2010;15(1–2):e93–7. doi:10.1007/BF03325286 20571329 | Intervention/Exposure
615 | Timlin MT, Pereira MA, Story M, Neumark-Sztainer D. Breakfast eating and weight change in a 5-year prospective analysis of adolescents: Project EAT (Eating Among Teens). Article. Pediatrics. 2008;121(3):e638–e645. doi:10.1542/peds.2007-1035 | Duplicate; Other; duplicate of refid 186
616 | Tin SP, Ho SY, Mak KH, Wan KL, Lam TH. Location of breakfast consumption predicts body mass index change in young Hong Kong children. Int J Obes (Lond). Jul 2012;36(7):925–30. doi:10.1038/ijo.2011.262 22234278 | Comparator
617 | Tinsley GM, Moore ML, Graybeal AJ, Time-restricted feeding plus resistance training in active females: a randomized trial. Am J Clin Nutr. Sep 1 2019;110(3):628–640. doi:10.1093/ajcn/nqz126 31268131 | Intervention/Exposure
618 | Togo P, Osler M, Sorensen TI, Heitmann BL. A longitudinal study of food intake patterns and obesityin adult Danish men and women. Int J Obes Relat Metab Disord. Apr 2004;28(4):583–93. doi:10.1038/sj.ijo.0802598 14770197 | Intervention/Exposure
619 | Torres L, Lee JL, Park S, Retention, Fasting Patterns, and Weight Loss With an IntermittentFasting App: Large-Scale, 52-Week Observational Study. JMIR Mhealth Uhealth. Oct 4 2022;10(10):e35896. doi:10.2196/35896 36194463 | Intervention/Exposure
620 | Toyoshima H, Masuoka N, Hashimoto S, Effect of the interaction between mental stress and eating pattern on body mass index gain in healthy Japanese male workers. J Epidemiol. 2009;19(2):88–93. doi:10.2188/jea.je20080066 19265270 | Study design; Intervention/Exposure
621 | Trier C, Fonvig CE, Bojsoe C, No influence of sugar, snacks and fast food intake on the degree of obesity or treatment effect in childhood obesity. Pediatr Obes. Dec 2016;11(6):506–512. doi:10.1111/ijpo.12094 26909660 | Intervention/Exposure
622 | Tsuzaki J, Maskarinec G, Mapa V, Diet Quality and Body Mass Index Over 20 Years in theMultiethnic Cohort. J Acad Nutr Diet. Feb 2024;124(2):194–204. doi:10.1016/j.jand.2023.02.001 36758897 | Intervention/Exposure
623 | Tucker LA, Bates L. Restrained eating and risk of gaining weight and body fat in middle-aged women: a 3-year prospective study. Am J Health Promot. Jan-Feb 2009;23(3):187–94. doi:10.4278/ajhp.07061456 19149424 | Intervention/Exposure
624 | Turner-McGrievy GM, Wirth MD, Bernhart JA, Aydin H. The Fasting and Shifted Timing (FAST) of Eating Study: A pilot feasibility randomized crossover intervention assessing the acceptability ofthree different fasting diet approaches. Appetite. Sep 1 2022;176:106135. doi:10.1016/j.appet.2022.106135 35716852 | Intervention/Exposure
625 | Unick JL, Jakicic JM, Marcus BH. Contribution of behavior intervention components to 24-month weight loss. Med Sci Sports Exerc. Apr 2010;42(4):745–53. doi:10.1249/MSS.0b013e3181bd1a57 19952841 | Intervention/Exposure
626 | Van Elten TM, Van Poppel MNM, Gemke R, Cardiometabolic Health in Relation to Lifestyleand Body Weight Changes 3(-)8 Years Earlier. Nutrients. Dec 10 2018;10(12)doi:10.3390/nu10121953 | Intervention/Exposure
627 | van Grieken A, Vlasblom E, Wang L, Personalized Web-Based Advice in Combination With Well-Child Visits to Prevent Overweight in Young Children: Cluster Randomized ControlledTrial. J Med Internet Res. Jul 27 2017;19(7):e268. doi:10.2196/jmir.7115 28751299 | Intervention/Exposure
628 | van Rossum CT, Hoebee B, Seidell JC, Genetic factors as predictors of weight gain in young adult Dutch men and women. Int J Obes Relat Metab Disord. Apr 2002;26(4):517–28. doi:10.1038/sj.ijo.0801964 12075579 | Intervention/Exposure
629 | Vanelli M, Monti G, Volta E, "GIOCAMPUS" - An effective school-based intervention for breakfast promotion and overweight risk reduction. Acta Biomed. Jan 23 2014;84(3):181–8.24458162 | Intervention/Exposure
630 | Veitsista A, Laitinen J, Sovio U, Roma E, Järvelin M-R, Bakoula C. Relationship between Eating Behavior, Breakfast Consumption, and Obesity Among Finnish and Greek Adolescents. J Nutr Educ Behav. 2010;42(6):417–421. doi:10.1016/j.jneb.2009.12.004 20729150 | Study design
631 | Verbestel V, De Coen V, Van Winckel M, Huybrechts I, Maes L, De Bourdeaudhuij I. Prevention of overweight in children younger than 2 years old: a pilot cluster-randomized controlled trial. Public Health Nutr. Jun 2014;17(6):1384–92. doi:10.1017/S1368980013001353 23701835 | Intervention/Exposure
632 | Vergetaki A, Linardakis M, Papadaki A, Kafatos A. Presence of metabolic syndrome and cardiovascularrisk factors in adolescents and University students in Crete (Greece), according todifferent levels of snack consumption. Appetite. Aug 2011;57(1):278–85. doi:10.1016/j.appet.2011.05.309 21640150 | Study design
633 | Verma N, Rastogi S. Effects of time-restricted meals and risk of metabolic diseases. Article. World Heart Journal. 2021;13(1):59–60. | Study design; Intervention/Exposure
634 | Versteeg RI, Ackermans MT, Nederveen AJ, Fliers E, Serlie MJ, la Fleur SE. Meal timing effectson insulin sensitivity and intrahepatic triglycerides during weight loss. Int J Obes (Lond). Feb 2018;42(2):156–162. doi:10.1038/ijo.2017.199 28811653 | Comparator; Duration
635 | Versteeg RI, Schrantee A, Adriaanse SM, Timing of caloric intake during weight loss differentially affects striatal dopamine transporter and thalamic serotonin transporter binding. FASEB J. Oct 2017;31(10):4545–4554. doi:10.1096/fj.201601234R 28679529 | Comparator; Duration
636 | Videon TM, Manning CK. Influences on adolescent eating patterns: the importance of family meals. J Adolesc Health. May 2003;32(5):365–73. doi:10.1016/s1054-139x(02)00711-5 12729986 | Study design; Intervention/Exposure
637 | Vidmar AP, Jones RB, Wee CP, Timing of food consumption in Hispanic adolescents with obesity. Pediatr Obes. Jul 2021;16(7):e12764. doi:10.1111/ijpo.12764 33370849 | Study design
638 | Vidmar AP, Naguib M, Raymond JK, Time-Limited Eating and Continuous Glucose Monitoring in Adolescents with Obesity: A Pilot Study. Nutrients. Oct 21 2021;13(11)doi:10.3390/nu13113697 | Intervention/Exposure
639 | Vieira Musse GN, Moreira T, Ayumi Kimura M, Skipping breakfast concomitant with late-night dinner eating is associated with worse outcomes following ST-segment elevation myocardialinfarction. Article. Eur J Prev Cardiol. 2020;27(19):2311–2313. doi:10.1177/2047487319839546 30995859 | Study design; Outcome; Health status
640 | Vilela S, Oliveira A, Ramos E, Moreira P, Barros H, Lopes C. Association between energy-dense food consumption at 2 years of age and diet quality at 4 years of age. Br J Nutr. Apr 14 2014;111(7):1275–82. doi:10.1017/S0007114513003620 24229473 | Intervention/Exposure
641 | Vilela S, Oliveira A, Severo M, Lopes C. Chrono-Nutrition: The Relationship between Time-of-Day Energy and Macronutrient Intake and Children's Body Weight Status. J Biol Rhythms. Jun 2019;34(3):332–342. doi:10.1177/0748730419838908 30917726 | Intervention/Exposure
642 | Vilela S, Severo M, Moreira T, Oliveira A, Hetherington MM, Lopes C. Association between eating frequency and eating behaviours related to appetite from 4 to 7 years of age: Findings fromthe population-based birth cohort generation XXI. Article. Appetite. Jan 1 2019;132:82–90. doi:10.1016/j.appet.2018.10.002 30296505 | Outcome
643 | Viskaal-van Dongen M, Kok FJ, de Graaf C. Effects of snack consumption for 8 weeks on energyintake and body weight. Int J Obes (Lond). Feb 2010;34(2):319–26. doi:10.1038/ijo.2009.243 19935746 | Intervention/Exposure; Comparator; Duration
644 | Vogels N, Diepvens K, Westerterp-Plantenga MS. Predictors of long-term weight maintenance. Obes Res. Dec 2005;13(12):2162–8. doi:10.1038/oby.2005.268 | Intervention/Exposure
645 | Vujovic N, Piron MJ, Qian J, Late isocaloric eating increases hunger, decreases energy expenditure, and modifies metabolic pathways in adults with overweight and obesity. Cell Metab. Oct 4 2022;34(10):1486–1498 e7. doi:10.1016/j.cmet.2022.09.007 36198293 | Intervention/Exposure; Comparator
646 | Waller SM, Vander Wal JS, Klurfeld DM, Evening ready-to-eat cereal consumption contributesto weight management. J Am Coll Nutr. Aug 2004;23(4):316–21. doi:10.1080/07315724.2004.10719374 15310735 | Comparator
647 | Wang Y, Ge K, Popkin BM. Why do some overweight children remain overweight, whereas others do not? Public Health Nutr. Sep 2003;6(6):549–58. doi:10.1079/phn2003470 14690036 | Intervention/Exposure
648 | Webb JB, Hardin AS. A preliminary evaluation of BMI status in moderating changes in body compositionand eating behavior in ethnically-diverse first-year college women. Eat Behav. Dec 2012;13(4):402–5. doi:10.1016/j.eatbeh.2012.06.004 23121798 | Intervention/Exposure
649 | Webber KH, Lee E. The diet quality of adult women participating in a behavioural weight-loss programme. J Hum Nutr Diet. Aug 2011;24(4):360–9. doi:10.1111/j.1365-277X.2011.01159.x 21414046 | Intervention/Exposure
650 | Wehrens SMT, Christou S, Isherwood C, Meal Timing Regulates the Human Circadian System. Curr Biol. Jun 19 2017;27(12):1768–1775 e3. doi:10.1016/j.cub.2017.04.059 28578930 | Comparator; Outcome
651 | Wei X, Lin B, Huang Y, Effects of Time-Restricted Eating on Nonalcoholic Fatty Liver Disease: The TREATY-FLD Randomized Clinical Trial. Journal article; Clinical trial protocol. JAMA Netw Open. Mar 1 2023;6(3):e233513. doi:10.1001/jamanetworkopen.2023.3513 36930148 | Intervention/Exposure
652 | Wen LM, Baur LA, Rissel C, Xu H, Simpson JM. Correlates of body mass index and overweight and obesity of children aged 2 years: findings from the healthy beginnings trial. Obesity (Silver Spring). Jul 2014;22(7):1723–30. doi:10.1002/oby.20700 24415528 | Intervention/Exposure
653 | Wengreen HJ, Moncur C. Change in diet, physical activity, and body weight among young-adults during the transition from high school to college. Nutr J. Jul 22 2009;8:32. doi:10.1186/1475-2891-8-32 19624820 | Study design
654 | Wennberg M, Gustafsson PE, Wennberg P, Hammarstrom A. Poor breakfast habits in adolescencepredict the metabolic syndrome in adulthood. Public Health Nutr. Jan 2015;18(1):122–9. doi:10.1017/S1368980013003509 24468205 | Intervention/Exposure
655 | Wennberg M, Gustafsson PE, Wennberg P, Hammarstrom A. Irregular eating of meals in adolescence and the metabolic syndrome in adulthood: results from a 27-year prospective cohort. Public Health Nutr. Mar 2016;19(4):667–73. doi:10.1017/S1368980015001445 25936413 | Intervention/Exposure
656 | Werneck AO, Agostinete RR, Cayres SU, Association between Cluster of Lifestyle Behaviorsand HOMA-IR among Adolescents: ABCD Growth Study. Medicina (Kaunas). Dec 1 2018;54(6)doi:10.3390/medicina54060096 | Study design
657 | Westerberg J, Edlund B, Ghaderi A. A 2-year longitudinal study of eating attitudes, BMI, perfectionism, asceticism and family climate in adolescent girls and their parents. Eat Weight Disord. Jun 2008;13(2):64–72. doi:10.1007/BF03327605 18612254 | Intervention/Exposure
658 | Westerberg-Jacobson J, Edlund B, Ghaderi A. A 5-year longitudinal study of the relationship between the wish to be thinner, lifestyle behaviours and disturbed eating in 9–20-year old girls. Eur Eat Disord Rev. May 2010;18(3):207–19. doi:10.1002/erv.983 20443204 | Intervention/Exposure
659 | Westerterp-Plantenga MS, Kovacs EM, Melanson KJ. Habitual meal frequency and energy intake regulation in partially temporally isolated men. Int J Obes Relat Metab Disord. Jan 2002;26(1):102–10. doi:10.1038/sj.ijo.0801855 11791154 | Study design; Intervention/Exposure
660 | Whetstone LM, Kolasa KM, Collier DN. Participation in community-originated interventions is associated with positive changes in weight status and health behaviors in youth. Am J Health Promot. Sep-Oct 2012;27(1):10–6. doi:10.4278/ajhp.100415-QUAN-117 22950920 | Intervention/Exposure
661 | White K, Wu B, Pilla SJ, Design and Implementation of a Time-Restricted Eating Interventionin a Randomized, Controlled Eating Study. Nutrients. Apr 20 2023;15(8)doi:10.3390/nu15081978 | Intervention/Exposure
662 | Wijga AH, Scholtens S, Bemelmans WJ, Diet, Screen Time, Physical Activity, and ChildhoodOverweight in the General Population and in High Risk Subgroups: Prospective Analyses in the PIAMA Birth Cohort. J Obes. 2010;2010doi:10.1155/2010/423296 | Intervention/Exposure
663 | Wijtzes AI, Jansen W, Jaddoe VW, Social Inequalities in Young Children's Meal Skipping Behaviors: The Generation R Study. PLoS One. 2015;10(7):e0134487. doi:10.1371/journal.pone.0134487 26225757 | Intervention/Exposure; Outcome
664 | Wilkinson M, Manoogian E, Zadourian A, Lo H, Panda S, Taub P. Time-Restricted Eating Promotes Weight Loss and Lowers Blood Pressure in Patients with Metabolic Syndrome. Journal of the American College of Cardiology. Mar 12 2019;73(9):1843–1843. doi:10.1016/S0735-1097(19)32449-0 | Intervention/Exposure; Publication status
665 | Wilkinson MJ, Manoogian ENC, Zadourian A, Ten-Hour Time-Restricted Eating Reduces Weight, Blood Pressure, and Atherogenic Lipids in Patients with Metabolic Syndrome. Cell Metab. Jan 7 2020;31(1):92–104 e5. doi:10.1016/j.cmet.2019.11.004 31813824 | Intervention/Exposure
666 | Williams SM, Taylor RW, Taylor BJ. Secular changes in BMI and the associations between risk factors and BMI in children born 29 years apart. Pediatr Obes. Feb 2013;8(1):21–30. doi:10.1111/j.2047-6310.2012.00081.x 23001951 | Intervention/Exposure
667 | Wing RR, Papandonatos G, Fava JL, Maintaining large weight losses: the role of behavioral and psychological factors. J Consult Clin Psychol. Dec 2008;76(6):1015–21. doi:10.1037/a0014159 19045969 | Intervention/Exposure
668 | Witbracht M, Keim NL, Forester S, Widaman A, Laugero K. Female breakfast skippers display adisrupted cortisol rhythm and elevated blood pressure. Physiol Behav. Mar 1 2015;140:215–21. doi:10.1016/j.physbeh.2014.12.044 25545767 | Outcome
669 | Wojcicki JM, Schwartz N, Jimenez-Cruz A, Bacardi-Gascon M, Heyman MB. Acculturation, dietary practices and risk for childhood obesity in an ethnically heterogeneous population of Latinoschool children in the San Francisco bay area. J Immigr Minor Health. Aug 2012;14(4):533–9. doi:10.1007/s10903-011-9553-7 22101726 | Study design
670 | Woo J, Cheung B, Ho S, Sham A, Lam TH. Influence of dietary pattern on the development of overweightin a Chinese population. Eur J Clin Nutr. Apr 2008;62(4):480–7. doi:10.1038/sj.ejcn.1602702 17327865 | Intervention/Exposure
671 | Woodruff SJ, Hanning RM. Effect of meal environment on diet quality rating. Can J Diet Pract Res. Autumn 2009;70(3):118–24. doi:10.3148/70.3.2009.118 19709467 | Study design
672 | Woodruff SJ, Hanning RM, Lambraki I, Storey KE, McCargar L. Healthy Eating Index-C is compromised among adolescents with body weight concerns, weight loss dieting, and meal skipping. Body Image. Dec 2008;5(4):404–8. doi:10.1016/j.bodyim.2008.04.006 18640883 | Outcome
673 | Wright CM, Cox KM, Sherriff A, To what extent do weight gain and eating avidity during infancypredict later adiposity? Public Health Nutr. Apr 2012;15(4):656–62. doi:10.1017/S1368980011002096 22005033 | Population Life Stage; Intervention/Exposure
674 | Wüenstel JW, Kowalkowska J, Wądołowska L, Słowińska MA, Niedźwiedzka E, Kurp L. Habitual eating of breakfast, consumption frequency of selected food and overweight prevalencein adolescents from various age groups. Dev Period Med. Apr-Jun 2015;19(2):193– 201.26384123 | Study design
675 | Wylie J, Barr S, Jeanes Y. Eating frequency and snacking habits in women with polycystic ovarysyndrome. J Hum Nutr Diet. 2009;22(3):274–275. doi:10.1111/j.1365-277x.2009.00952_25.x | Publication status
676 | Xiao Q, Bauer C, Layne T, Playdon M. The association between overnight fasting and body mass index in older adults: the interaction between duration and timing. Int J Obes (Lond). Mar 2021;45(3):555–564. doi:10.1038/s41366-020-00715-z 33214704 | Intervention/Exposure; Comparator
677 | Xiao Q, Garaulet M, Scheer F. Meal timing and obesity: interactions with macronutrient intake and chronotype. Int J Obes (Lond). Sep 2019;43(9):1701–1711. doi:10.1038/s41366-018-0284-x 30705391 | Intervention/Exposure
678 | Xie Z, Sun Y, Ye Y, Randomized controlled trial for time-restricted eating in healthy volunteerswithout obesity. Nat Commun. Feb 22 2022;13(1):1003. doi:10.1038/s41467-022-28662-5 35194047 | Intervention/Exposure
679 | Xinyuan Z, Yuntao W, Muzi N, Habitual Night Eating Was Positively Associated With Progressof Arterial Stiffness in Chinese Adults. J Am Heart Assoc. 2020;9(19):1–13. doi:10.1161/JAHA.120.016455 | Intervention/Exposure; Outcome
680 | Xu S, Jiang Y, Zhang Y, Dietary recommendations for fasting days in an alternate-day intermittentfasting pattern: A randomized controlled trial. Nutrition. Oct 2022;102:111735. doi:10.1016/j.nut.2022.111735 35816815 | Intervention/Exposure
681 | Xue H, Maguire RL, Liu J, Snacking frequency and dietary intake in toddlers and preschool children. Appetite. Nov 1 2019;142:104369. doi:10.1016/j.appet.2019.104369 31302102 | Study design; Outcome
682 | Yan Z, Harrington A. Factors that predict weight gain among first-year college students. Article. Health Education Journal. 2020;79(1):94–103. doi:10.1177/0017896919865758 | Study design
683 | Yasuda J, Gomi T, Kotemori A, Breakfast before resistance exercise lessens urinary markers of muscle protein breakdown in young men: A crossover trial. Article. Nutrition. 2021;83doi:10.1016/j.nut.2020.111088 | Intervention/Exposure; Outcome
684 | Yokoro M, Wakimoto K, Otaki N, Fukuo K. Increased Prevalence of Breakfast Skipping in FemaleCollege Students in COVID-19. Article. Asia Pac J Public Health. May 2021;33(4):438–440. doi:10.1177/1010539521998861 33666099 | Study design
685 | Yoon C, Jacobs DR Jr., Duprez DA, Questionnaire-based problematic relationship to eating and food is associated with 25 year body mass index trajectories during midlife: The Coronary Artery Risk Development In Young Adults (CARDIA) Study. Int J Eat Disord. Jan 2018;51(1):10–17. doi:10.1002/eat.22813 29215750 | Intervention/Exposure
686 | Yoon C, Mason SM, Hooper L, Eisenberg ME, Neumark-Sztainer D. Disordered Eating Behaviors and 15-year Trajectories in Body Mass Index: Findings From Project Eating and Activityin Teens and Young Adults (EAT). J Adolesc Health. Feb 2020;66(2):181–188. doi:10.1016/j.jadohealth.2019.08.012 31630924 | Intervention/Exposure
687 | Yoon SR, Choi M, Kim OY. Effect of Breakfast Consumption and Meal Time Regularity on Nutrient Intake and Cardiometabolic Health in Korean Adults. J Lipid Atheroscler. May 2021;10(2):240–250. doi:10.12997/jla.2021.10.2.240 34095015 | Study design
688 | Yoshinaga M, Hatake S, Tachikawa T, Shinomiya M, Miyazaki A, Takahashi H. Impact of lifestylesof adolescents and their parents on cardiovascular risk factors in adolescents. J Atheroscler Thromb. 2011;18(11):981–90. doi:10.5551/jat.9514 21836372 | Study design
689 | Yoshizaki T, Togo F. Objectively measured chronotype and social jetlag are associated with habitualdietary intake in undergraduate students. Nutr Res. Jun 2021;90:36–45. doi:10.1016/j.nutres.2021.04.003 34038836 | Study design; Intervention/Exposure
690 | Yu HJ, Liu X, Zheng M, Zhang MZ, Liu MW, He QQ. Child neglect and eating habits in primary schoolchildren: A prospective study in Wuhan, China. Appetite. Jan 1 2022;168:105756. doi:10.1016/j.appet.2021.105756 34648908 | Intervention/Exposure; Outcome
691 | Zakrzewski JK, Gillison FB, Cumming S, Associations between breakfast frequency and adiposity indicators in children from 12 countries. Int J Obes Suppl. Dec 2015;5(Suppl 2):S80–8. doi:10.1038/ijosup.2015.24 27152190 | Study design
692 | Zakrzewski-Fruer JK, Wells EK, Crawford NSG, Afeef SM, Tolfrey K. Physical activity duration but not energy expenditure differs between daily and intermittent breakfast consumption in adolescent girls: A randomized crossover trial. Article. J Nutr. 2018;148(2):236–244. doi:10.1093/JN/NXX055 29490105 | Outcome
693 | Zalewska M, Maciorkowska E. Dietary Habits and Physical Activity of 18-Year-Old Adolescents in Relation to Overweight and Obesity. Iran J Public Health. May 2019;48(5):864–872.31523643 | Study design
694 | Zappalá G, Platania A, Bellia MA, Ragusa R, Marranzano M. Eating habits and food intake in relationto adherence to the mediterranean diet, in adults living in the Island of Sicily. Article. Mediterranean Journal of Nutrition and Metabolism. 2019;12(3):271–281. doi:10.3233/MNM-190306 | Study design
695 | Zeb F, Wu X, Chen L, Effect of time-restricted feeding on metabolic risk and circadian rhythmassociated with gut microbiome in healthy males. Br J Nutr. Jun 14 2020;123(11):1216– 1226. doi:10.1017/S0007114519003428 31902372 | Intervention/Exposure
696 | Zeron-Rugerio MF, Longo-Silva G, Hernaez A, Ortega-Regules AE, Cambras T, Izquierdo-Pulido M. The Elapsed Time between Dinner and the Midpoint of Sleep is Associated with Adiposityin Young Women. Nutrients. Feb 5 2020;12(2)doi:10.3390/nu12020410 | Study design; Intervention/Exposure
697 | Zerva A, Nassis GP, Krekoukia M, Psarra G, Sidossis LS. Effect of eating frequency on body composition in 9–11-year-old children. Int J Sports Med. Mar 2007;28(3):265–70. doi:10.1055/s-2006-924349 17024645 | Study design
698 | Zha P, Mahat G, Chao Y-Y, Iovino C. Perceived Body Weight and Weight Management-Related Behaviors among Young Adults: Mediating Effects of Body Mass Index. Am J Health Educ. 2022;53(6):381–393. doi:10.1080/19325037.2022.2120120 | Study design; Intervention/Exposure; Outcome
699 | Zhang LM, Liu Z, Wang JQ, Randomized controlled trial for time-restricted eating in overweightand obese young adults. iScience. Sep 16 2022;25(9):104870. doi:10.1016/j.isci.2022.104870 36034217 | Intervention/Exposure
700 | Zhao L, Hutchison AT, Liu B, Time-restricted eating alters the 24-hour profile of adipose tissuetranscriptome in men with obesity. Obesity (Silver Spring). Feb 2023;31 Suppl 1(Suppl 1):63–74. doi:10.1002/oby.23499 35912794 | Intervention/Exposure
701 | Zhao L, Hutchison AT, Liu B, Time-restricted eating improves glycemic control and dampens energy-consuming pathways in human adipose tissue. Nutrition. Apr 2022;96:111583. doi:10.1016/j.nut.2021.111583 35150947 | Intervention/Exposure
702 | Zhao L, Hutchison AT, Wittert GA, Intermittent Fasting Does Not Uniformly Impact Genes Involved in Circadian Regulation in Women with Obesity. Obesity (Silver Spring). Jul 2020;28 Suppl 1:S63–S67. doi:10.1002/oby.22775 32438531 | Intervention/Exposure
703 | Zheng J, Gao L, Xue H, Eating-out behaviors, associated factors and associations with obesityin Chinese school children: findings from the childhood obesity study in China mega-cities. Eur J Nutr. Sep 2021;60(6):3003–3012. doi:10.1007/s00394-020-02475-y | Intervention/Exposure
704 | Zilberter T, Zilberter EY. Breakfast: to skip or not to skip? Front Public Health. 2014;2:59. doi:10.3389/fpubh.2014.00059 24918099 | Study design