# Appendix 1 Abbreviations

Table A 1 List of abbreviations
Abbreviation: Full name
BMI: Body mass index
GWG: Gestational weight gain
HHS: United States Department of Health and Human Services
NESR: Nutrition Evidence Systematic Review
USDA: United States Department of Agriculture