# References of the articles included in the systematic review

### Infants, children, and adolescents

1 Davis JN, Asigbee FM, Markowitz AK, . Consumption of artificial sweetened beverages associated with adiposity and increasing HbA1c in Hispanic youth. Clin Obes. Aug 2018;8(4):236–243. doi:10.1111/cob.12260 29896938

### Adults and older adults

2 Ebbeling CB, Feldman HA, Steltz SK, Quinn NL, Robinson LM, Ludwig DS. Effects of sugar-sweetened, artificially sweetened, and unsweetened beverages on cardiometabolic risk factors, body composition, and sweet taste preference: A randomized controlled trial. J Am Heart Assoc. Aug 4 2020;9(15):e015668. doi:10.1161/JAHA.119.015668 32696704
3 Engel S, Tholstrup T, Bruun JM, Astrup A, Richelsen B, Raben A. Effect of high milk and sugar-sweetened and non-caloric soft drink intake on insulin sensitivity after 6 months in overweight and obese adults: a randomized controlled trial. Eur J Clin Nutr. Mar 2018;72(3):358–366. doi:10.1038/s41430-017-0006-9 29235560
4 Harrold JA, Hill S, Radu C, . Effects of non-nutritive sweetened beverages versus water after a 12-week weight-loss program: A randomized controlled trial. Obesity (Silver Spring). Aug 2023;31(8):1996–2008. doi:10.1002/oby.23796 37475684
5 Harrold JA, Hill S, Radu C, . Non-nutritive sweetened beverages versus water after a 52-week weight management programme: a randomised controlled trial. Int J Obes (Lond). Jan 2024;48(1):83–93. doi:10.1038/s41366-023-01393-3 37794246
6 Kendig MD, Chow JYL, Martire SI, Rooney KB, Boakes RA. Switching from sugar- to artificially-sweetened beverages: A 12-week trial. Nutrients. May 4 2023;15(9) doi:10.3390/nu15092191
7 Madjd A, Taylor MA, Delavari A, Malekzadeh R, Macdonald IA, Farshchi HR. Effects on weight loss in adults of replacing diet beverages with water during a hypoenergetic diet: a randomized, 24-wk clinical trial. Am J Clin Nutr. Dec 2015;102(6):1305–12. doi:10.3945/ajcn.115.109397 26537940
8 Madjd A, Taylor MA, Delavari A, Malekzadeh R, Macdonald IA, Farshchi HR. Effects of replacing diet beverages with water on weight loss and weight maintenance: 18-month follow-up, randomized clinical trial. Int J Obes (Lond). Apr 2018;42(4):835–840. doi:10.1038/ijo.2017.306 29633983
9 Peters JC, Beck J, Cardel M, . The effects of water and non-nutritive sweetened beverages on weight loss and weight maintenance: A randomized clinical trial. Obesity (Silver Spring). Feb 2016;24(2):297–304. doi:10.1002/oby.21327 26708700
10 Peters JC, Wyatt HR, Foster GD, . The effects of water and non-nutritive sweetened beverages on weight loss during a 12-week weight loss treatment program. Obesity (Silver Spring). Jun 2014;22(6):1415–21. doi:10.1002/oby.20737 24862170
11 Tate DF, Turner-McGrievy G, Lyons E, . Replacing caloric beverages with water or diet beverages for weight loss in adults: main results of the Choose Healthy Options Consciously Everyday (CHOICE) randomized clinical trial. Am J Clin Nutr. Mar 2012;95(3):555–63. doi:10.3945/ajcn.111.026278 22301929
12 Viveros-Watty PE, Lopez-Franco O, Zepeda RC, . Effects on cardiometabolic risk factors after reduction of artificially sweetened beverage consumption in overweight subjects. A randomised controlled trial. Endocrinol Diabetes Nutr (Engl Ed). Mar 2022;69(3):168–177. doi:10.1016/j.endien.2022.02.015 35396115
13 Bazzano LA, Li TY, Joshipura KJ, Hu FB. Intake of fruit, vegetables, and fruit juices and risk of diabetes in women. Diabetes Care. Jul 2008;31(7):1311–7. doi:10.2337/dc08-0080 18390796
14 Bhupathiraju SN, Pan A, Malik VS, . Caffeinated and caffeine-free beverages and risk of type 2 diabetes. Am J Clin Nutr. Jan 2013;97(1):155–66. doi:10.3945/ajcn.112.048603 23151535
15 Chen Z, Khandpur N, Desjardins C, . Ultra-processed food consumption and risk of type 2 diabetes: Three large prospective U.S. cohort studies. Diabetes Care. Jul 1 2023;46(7):1335–1344. doi:10.2337/dc22-1993 36854188
16 de Koning L, Malik VS, Rimm EB, Willett WC, Hu FB. Sugar-sweetened and artificially sweetened beverage consumption and risk of type 2 diabetes in men. Am J Clin Nutr. Jun 2011;93(6):1321–7. doi:10.3945/ajcn.110.007922 21430119
17 Drouin-Chartier JP, Zheng Y, Li Y, . Changes in consumption of sugary beverages and artificially sweetened beverages and subsequent risk of type 2 diabetes: Results from three large prospective U.S. cohorts of women and men. Diabetes Care. Dec 2019;42(12):2181–2189. doi:10.2337/dc19-0734 31582428
18 Fagherazzi G, Vilier A, Saes Sartorelli D, Lajous M, Balkau B, Clavel-Chapelon F. Consumption of artificially and sugar-sweetened beverages and incident type 2 diabetes in the Etude Epidemiologique aupres des femmes de la Mutuelle Generale de l’Education Nationale-European Prospective Investigation into Cancer and Nutrition cohort. Am J Clin Nutr. Mar 2013;97(3):517–23. doi:10.3945/ajcn.112.050997 23364017
19 Gardener H, Moon YP, Rundek T, Elkind MSV, Sacco RL. Diet soda and sugar-sweetened soda consumption in relation to incident diabetes in the Northern Manhattan Study. Curr Dev Nutr. May 2018;2(5):nzy008. doi:10.1093/cdn/nzy008 29955723
20 Hirahatake KM, Jacobs DR, Shikany JM, . Cumulative intake of artificially sweetened and sugar-sweetened beverages and risk of incident type 2 diabetes in young adults: the Coronary Artery Risk Development In Young Adults (CARDIA) Study. Am J Clin Nutr. Sep 1 2019;110(3):733–741. doi:10.1093/ajcn/nqz154 31374564
21 Huang M, Quddus A, Stinson L, . Artificially sweetened beverages, sugar-sweetened beverages, plain water, and incident diabetes mellitus in postmenopausal women: the prospective Women’s Health Initiative observational study. Am J Clin Nutr. Aug 2017;106(2):614–622. doi:10.3945/ajcn.116.145391 28659294
22 Imamura F, Schulze MB, Sharp SJ, . Estimated substitution of tea or coffee for sugar-sweetened beverages was associated with lower type 2 diabetes incidence in case-cohort analysis across 8 European countries in the EPIC-InterAct Study. J Nutr. Nov 1 2019;149(11):1985–1993. doi:10.1093/jn/nxz156 31396627
23 InterAct C, Romaguera D, Norat T, . Consumption of sweet beverages and type 2 diabetes incidence in European adults: results from EPIC-InterAct. Diabetologia. Jul 2013;56(7):1520–30. doi:10.1007/s00125-013-2899-8 23620057
24 Jensen PN, Howard BV, Best LG, . Associations of diet soda and non-caloric artificial sweetener use with markers of glucose and insulin homeostasis and incident diabetes: the Strong Heart Family Study. Eur J Clin Nutr. Feb 2020;74(2):322–327. doi:10.1038/s41430-019-0461-6 31253876
25 McNaughton SA, Mishra GD, Brunner EJ. Dietary patterns, insulin resistance, and incidence of type 2 diabetes in the Whitehall II Study. Diabetes Care. Jul 2008;31(7):1343–8. doi:10.2337/dc07-1946 18390803
26 Nettleton JA, Lutsey PL, Wang Y, Lima JA, Michos ED, Jacobs DR, Jr. Diet soda intake and risk of incident metabolic syndrome and type 2 diabetes in the Multi-Ethnic Study of Atherosclerosis (MESA). Diabetes Care. Apr 2009;32(4):688–94. doi:10.2337/dc08-1799 19151203
27 O’Connor L, Imamura F, Lentjes MA, Khaw KT, Wareham NJ, Forouhi NG. Prospective associations and population impact of sweet beverage intake and type 2 diabetes, and effects of substitutions with alternative beverages. Diabetologia. Jul 2015;58(7):1474–83. doi:10.1007/s00125-015-3572-1 25944371
28 Palmer JR, Boggs DA, Krishnan S, Hu FB, Singer M, Rosenberg L. Sugar-sweetened beverages and incidence of type 2 diabetes mellitus in African American women. Arch Intern Med. Jul 28 2008;168(14):1487–92. doi:10.1001/archinte.168.14.1487 18663160
29 Pan A, Malik VS, Schulze MB, Manson JE, Willett WC, Hu FB. Plain-water intake and risk of type 2 diabetes in young and middle-aged women. Am J Clin Nutr. Jun 2012;95(6):1454–60. doi:10.3945/ajcn.111.032698 22552035
30 Rose BD, Rimm EB, Zhang X, . You are What You Drink? How Associations Between Profiles of Beverage Consumption and Type 2 Diabetes Risk are Mediated by Biomarker Networks. Am J Clin Nutr. Jul 2023;118(1):68–76. doi:10.1016/j.ajcnut.2023.04.015 37061165
31 Sakurai M, Nakamura K, Miura K, . Sugar-sweetened beverage and diet soda consumption and the 7-year risk for type 2 diabetes mellitus in middle-aged Japanese men. Eur J Nutr. Feb 2014;53(1):251–8. doi:10.1007/s00394-013-0523-9 23575771
32 Schulze MB, Manson JE, Ludwig DS, . Sugar-sweetened beverages, weight gain, and incidence of type 2 diabetes in young and middle-aged women. JAMA. Aug 25 2004;292(8):927–34. doi:10.1001/jama.292.8.927 15328324
33 von Ruesten A, Feller S, Bergmann MM, Boeing H. Diet and risk of chronic diseases: results from the first 8 years of follow-up in the EPIC-Potsdam study. Eur J Clin Nutr. Apr 2013;67(4):412–9. doi:10.1038/ejcn.2013.7 23388667