# Summary of conclusion statements and grades

The Committee answered the systematic review question, “What is the relationship between low- and no-calorie-sweetened beverage consumption and risk of type 2 diabetes?”, with the following conclusion statements.^*^ The grades reflect the strength of the evidence underlying the conclusion statements.

* A conclusion statement is carefully constructed, based on the evidence reviewed, to answer the systematic review question. A conclusion statement does not draw implications and should not be interpreted as dietary guidance.

### Infants, children, and adolescents

A conclusion statement cannot be drawn about the relationship between low- and no-calorie sweetened beverage consumption by infants, children, and adolescents and risk of type 2 diabetes because there is not enough evidence available. (Grade: Grade Not Assignable)

### Adults and older adults

Low- and no-calorie sweetened beverage consumption by adults and older adults may not be associated with risk of type 2 diabetes. This conclusion statement is based on evidence graded as limited. (Grade: Limited)

## Research recommendations

The Committee identified the following research recommendations that describe the research, data, and methodological advances that are needed to strengthen the body of evidence on low- and no-calorie sweetened beverage consumption and risk of type 2 diabetes.

1. Examine low- and no-calorie sweetened beverage intake in childhood (from birth to adolescence) in relation to changes in risk of type 2 diabetes across a range of ages and life stages.
2. Conduct well-controlled, randomized interventions, particularly in the United States with diverse populations, to examine the effect of low- and no-calorie sweetened beverage consumption and risk of type 2 diabetes.
3. Include diverse populations with varying race and/or ethnicity and socioeconomic position.
4. Control for confounding factors, such as family history of diabetes, that may impact the relationship between low- and no-calorie sweetened beverage consumption and risk of type 2 diabetes.
5. Provide repeated measures of beverage intake using validated dietary assessment tools and methods throughout the course of follow-up.
6. Use clear, specific definitions for low- and no-calorie sweetened beverages.

Table 7 Evidence examining relationship between low- and no-calorie sweetened beverage consumption in infants, children, and adolescents and risk of type 2 diabetes^a^

Study and Participant Characteristics | Exposure, Comparator, and Outcome(s) | Results | Methodological Considerations
Davis, 2018^1^; PCS, SOLAR (Study of Latino Adolescents at Risk for Diabetes), U.S. Analytic N=98; Study objective: To determine which aspects of dietary carbohydrate, specifically dietary sugar, fiber, glycemic index, or glycemic load, are associated with adiposity and insulin dynamics in overweight Latino children; Participant characteristics at baseline: adolescents with overweight or obesity; - Age (mean and/or range): 14.0 (1.8)y; 12-18y; - Female: 43%; - Race and/or ethnicity: 100% Hispanic; - Socioeconomic position: NR; - Anthropometry: All with BMI ≥85th percentile; 17% with overweight, 84% with obesity; - Physical activity: NR; - Family history of diabetes: 100%; - Smoking: NR; - TEI: ~1800 kcal/d; - Beverage intake at baseline: 1.4 (0.8) svg/d among chronic ASB consumers (9% of sample); Excluded from study or analysis: <8 or >18y; BMI <85th percentile for age and sex; non-Hispanic ancestry; no family history of T2D; missing data; medication or disease diagnosis known to affect body composition | Exposure: Artificial sweetened beverages (ASB, including those found in sodas, coffees, energy drinks, teas, sports drinks, juices, and flavored waters); - Serving Size: 8oz; Comparator: categorical intake (No ASB, ASB initiators, chronic ASB consumers); - No ASB/Control (n=75): no ASB at baseline or 1y follow-up; - ASB initiators (n=14): no ASB at baseline but started drinking ASB at 1y follow-up; - Chronic ASB consumers (n=9): consumed ASB at baseline and 1y follow-up; Assessment methods and timing:; - Two 24-hour dietary recalls; - Baseline, 1y follow-up; Outcome assessment methods and timing:; - Fasting blood samples and 120-min OGTT were collected using standard methods. Glucose and insulin IAUC were calculated from frequently sampled intravenous glucose tolerance tests. The MINMOD MILLENIUM 2003 computer program was used to determine insulin sensitivity, acute insulin response, and disposition index of β-cell function.; - Baseline, 1y follow-up | All Mean (SD): Baseline, 1yr; [underlined: Change in fasting blood glucose] [underlined: (mg/dL)]; No ASB: 92.5 (7.3), 88.7 (9.0); ASB Initiators: 91.9 (8.3), 84.6 (8.1); Chronic ASB: 91.9 (6.6), 85.0 (4.3); P (group) = 0.67; P-interaction = 0.47; [underlined: Change in fasting insulin (μmol/mL)]; No ASB: 13.6 (10.3), 14.2 (10.0); ASB Initiators: 15.6 (8.0), 20.1 (23.6); Chronic ASB: 16.3 (11.1), 13.8 (10.3); P (group) = 0.36; P-interaction = 0.51; [underlined: Change in 2h OGTT (mg/dL)]; No ASB: 124.2 (21.5), 118.4 (23.2); ASB Initiators: 126.9 (28.8), 127.9 (20.9); Chronic ASB: 122.3 (19.8), 110.1 (25.6); P (group) = 0.46; P-interaction = 0.46; [underlined: Change in glucose IAUC (nmol/min-L)]; No ASB: 79.9 (35.5), 80.5 (34.9); ASB Initiators: 77.5 (18.7), 86.2 (25.3); Chronic ASB: 76.0 (40.5), 73.5 (35.8); P (group) = 0.89; P-interaction = 0.93; [underlined: Change in insulin IAUC (nmol/min-L)]; No ASB: 277.7 (199.9), 243.4 (157.7); ASB Initiators: 281.9 (192.6), 256.7 (154.8); Chronic ASB: 345.6 (262.5), 316.4 (424.3); P (group) = 0.57; P-interaction = 0.98; [underlined: Change in HbA1C]; No ASB: 5.5 (0.4), 5.5 (0.4); ASB Initiators: 5.4 (0.3), 5.5 (0.4); Chronic ASB: 5.1 (0.2), 5.4 (0.3); P (group) = 0.28; P-interaction = 0.01 | Model adjustments:; - TEI: yes; - Key confounders: sex, race and/or ethnicity, anthropometry, family history of diabetes; - Other: Tanner stage; Limitations:; - Did not account for key confounders: age, socioeconomic position, physical activity; - No evidence whether the result was biased due to missing data; - No preregistered data analysis plan; Funding:; NIDDK; General Clinical Research Center for Health Resources; Results were also provided for change in insulin sensitivity, acute insulin response, and disposition index of β-cell function: all P=NS for group and group x time.

a Abbreviations: ASB: artificial sweetened beverage(s); BMI: body mass index; d: day(s); dL: deciliter(s); PCS: prospective cohort study; HbA1C: hemoglobin A1C; IAUC: incremental area under the curve; kcal: kilocalorie(s); L: liter(s); LNCSB: low- and no-calorie sweetened beverage(s); mg: milligram(s); min: minute(s); mL: milliliter(s); NA: not applicable; NIDDK: National Institute of Diabetes and Digestive and Kidney Diseases; nmol: nanomole(s); NR: not reported; NS: not significant; OGTT: oral glucose tolerance test; PCS: prospective cohort study; SD: standard deviation; svg: serving(s); T2D: type 2 diabetes; TEI: total energy intake; μmol: micromole(s); wk: week(s); y: year(s)

Table 8 Risk of bias for observational studies examining low- and no-calorie sweetened beverage consumption in infants, children, and adolescents and risk of type 2 diabetes^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of reported result | Overall risk of bias
Davis, 2018^1^ | HIGH | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH

a Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the “Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)” tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi:10.1016/j.envint.2024.108602. )

Table 9 Intervention studies examining the relationship between low- and no-calorie sweetened beverage consumption in adults and older adults and risk of type 2 diabetes^a^

Study and Participant Characteristics | Intervention, Comparator, and Outcome(s) | Results | Methodological Considerations
Ebbeling, 2020^2^; RCT-Parallel, U.S.; Baseline N=203, Analytic N=186 (Attrition: 8%); Study objective: To compare effects of consuming SSB, artificially-sweetened beverages, and unsweetened beverages in adults who habitually consumed SSB; Participant characteristics at baseline: adults that habitually consume SSB; - Age (mean and/or range): ~27y; 18-40y; - Female: 40%; - Race and/or ethnicity: 51% White; 20% Black; 13% Asian; 17% Multiple/other/unknown; 12% Hispanic; - Socioeconomic position: 53% with bachelors degree or higher; 31% with some college, vocational school, or associate’s degree; 27% with household income ≥$60k/yr; - Anthropometry: BMI ~26 (5) kg/m^2^; - Physical activity: NR; - Family history of diabetes: NR; - Smoking: NR; - Alcohol intake: NR; - TEI: ~2100 (650) kcal/d; - Beverage intake at baseline: ~0.2 (0.4) svg/d (12-oz svg); Excluded from study or analysis: BMI <18.5 or >40 kg/m^2^; SSB consumption less than one 12-oz svg/d; FBG ≥110 mg/dL, physician diagnosis of a major medical or psychiatric illness; chronic use of any medication that could affect study outcomes; smoking >10 cigarettes/d; pregnancy (preceding 12mo) or plans to become pregnant during study period; lactation (preceding 3mo); change in hormonal contraceptives (preceding 3mo) | Intervention: LNCSB (n=60): artificially-sweetened/diet beverages; participants instructed to drink LNCSB delivered to home and to not drink SSB; - Serving Size: 12oz; participants were instructed to drink delivered beverages at the same rate (number of svg/d) as usual SSB consumption; Comparator: Water (n=66): spring water, purified water, and unsweetened sparking water with or without flavoring): participants instructed to drink water delivered to home and to not drink SSB or LNCSB; Duration: 52wk; Compliance: Biweekly check-in telephone calls to review beverage consumption; NS difference between groups in number of beverage deliveries or check-in calls completed; Outcome assessment methods and timing:; - Fasting blood samples were collected and HOMA was calculated to assess insulin sensitivity; - Baseline, 52wk follow-up | [underlined: Change in fasting glucose (mg/dL) over 12mo],; Mean (SE); Water: 1.8 (0.7), P=0.01; LNCSB: 0.9 (0.8), P=0.24; Between groups: P=0.63; C[underlined: hange in fasting insulin (μIU/L) over 12mo], Mean (SE); Water: -0.0 (6.4), P=0.99; LNCSB: -5.4 (6.3), P=0.39; Between groups: P=0.37; [underlined: Change in insulin sensitivity % over 12mo], Mean(SE); Water: -0.6 (6.3), P=0.93; LNCSB: 4.9 (6.9), P=0.46; Between groups: P=0.38 | Model adjustments:; - TEI: no; Limitations:; - Methods for randomization and concealment NR; - Not sufficiently powered; - Trial registry did not include data analysis plan; Funding:; NHLBI; NIDDK;; National Center for Research Resources; Harvard Catalyst Clinical and Translational Science Center; New Balance Foundation
Engel, 2018^3^; RCT-Parallel, Denmark; Baseline N=73, Analytic N=58 (Attrition: 21%); Study objective: To investigate the long-term effects of semi-skimmed milk on insulin sensitivity and further to compare milk with sugar-sweetened soft drinks and non-caloric soft drinks; Participant characteristics at baseline: adults with overweight and obesity; - Age (mean and/or range): ~39y; 20-50y; - Female: 64%; - Race and/or ethnicity: NR; - Socioeconomic position: NR; - Anthropometry: BMI ~32 kg/m^2^; - Physical activity: NR; - Family history of diabetes: NR; - Smoking: All nonsmokers; - Alcohol intake: ~8 g/d (NS difference between groups); - TEI: ~2450 kcal/d; - Beverage intake at baseline: NR; Excluded from study or analysis: <20 or >50y; BMI <26 or >40 kg/m^2^; diabetes; blood pressure >160/100 mmHg; medication affecting either blood lipids, blood glucose or body weight; smoking; pregnancy or breastfeeding; allergies to milk or suffering from phenylketonuria; excessive physical activity (>10 hr/wk) | Intervention: Artificially-sweetened non-caloric soft drinks (NCSD, n=15): aspartame-sweetened diet cola (Coca Colas); - Serving Size: 1 L/d; Comparator: Water (n=16): still mineral water (Aqua d’or; 1 L/d); Duration: 26wk; Compliance: Empty bottles or cartons every 3-4wk; 7-d dietary records at baseline, 3mo, 6mo; data NR; Outcome assessment methods and timing:; - Fasting blood samples were collected and 120-min OGTT was conducted to assess various measures of insulin sensitivity (Matsuda Index, fasting, and AUC glucose, insulin and homeostasis model assessment values).; - Baseline, 6mo follow-up | [underlined: Change in fasting glucose (mmol/L)], Mean (SE); Within group: Baseline, 6mo; Water: 5.26 (0.54), 5.35 (0.15); NCSD: 5.52 (0.47), 5.49 (0.15); Between groups, change over 6mo: P=NS; [underlined: Change in fasting insulin (pmol/L)], Mean (SE); Within group: Baseline, 6mo; Water: 68.09 (54.67), 93.19 (24.94); NCSD: 75.35 (30.64), 74.73 (10.13); Between groups, change over 6mo: P=NS; [underlined: Change in AUC OGTT glucose (mmol/L)], Mean (SE); Within group: Baseline, 6mo; Water: 829 (204), 812 (62); NCSD: 864 (214), 876 (61); Between groups, change over 6mo: P=NS; [underlined: Change in AUC OGTT insulin (pmol/L)], Mean (SE); Within group: Baseline, 6mo; Water: 25,784 (10,735), 17,786 (2726); NCSD: 32,396 (12,305), 22,766 (3090); Between groups, change over 6mo: P=NS; [underlined: Change in Matsuda Index], Mean (SE); Within group: Baseline, 6mo; Water: 7.98 (4.07), 8.38 (1.27); NCSD: 6.01 (3.55), 6.14 (0.84); Between groups, change over 6mo: P=NS; [underlined: Change in HOMA-IR], Mean (SE); Within group: Baseline, 6mo; Water: 1.29 (1.04), 1.71 (0.44); NCSD: 1.44 (0.58), 1.42 (0.19); Between groups, change over 6mo: P=NS; [underlined: Change in HOMA-IR AUC], Mean (SE); Within group: Baseline, 6mo; Water: 3.08 (3.26), 3.08 (0.82); NCSD: 2.58 (1.50), 2.58 (0.39); Between groups, change over 6mo: P=NS | Model adjustments:; - TEI: yes (NS difference between groups); Limitations:; - Methods for randomization and concealment NR; - No evidence whether the result was biased due to missing data; - No power calculation; - Trial registry did not include data analysis plan; Funding:; Danish Council for Strategic Research; The Food Study Group/Danish Ministry of Food, Agriculture and Fisheries; Novo Nordic Foundation; Clinical Institute at Aarhus University, Denmark; Danish Dairy Company, Arla Foods
Harrold, 2023^4^; RCT-Parallel, SWITCH Trial (The effectS of non-nutritive sWeetened beverages on appetITe during aCtive weigHt loss), UK; Baseline N=493, Analytic N=196 (Attrition: 60%, impacted by COVID-19 pandemic); Study objective: To compare non-nutritive sweetened beverages versus water for weight loss after a 12-week behavioral weight-management program; Participant characteristics at baseline: adults with overweight and obesity; - Age (mean and/or range): ~45y; 18-65y; - Female: 70%; - Race and/or ethnicity: NR; - Socioeconomic position: NR; - Anthropometry: BMI 31 (2) kg/m^2^; - Physical activity: ~8250 steps/d; - Family history of diabetes: NR; - Smoking: All nonsmokers; - Alcohol intake: NR; - TEI: NR; - Beverage intake at baseline: All drink <2 L/d of NNS (inclusion criteria); 24% were NNS naïve (NNS ≤25% of drink choices in 5y before screening); Excluded from study or analysis: <18 or >65y; BMI <27 or >35 kg/m^2^; drinking chilled beverages <3/wk; first-year university student; diabetes, gastrointestinal or cardiovascular disease; bariatric surgery; medication or supplements known to affect weight; pregnant or breastfeeding; food allergies or intolerances; recent or current smokers; dieting or significant weight loss; regular intense exercise; working in appetite or feeding-related disciplines; food-avoidance diet, abnormal eating behavior, or non-breakfast eaters | Intervention: Non-nutritive sweetened beverages (NNS): ≥2 svg/d; participants could select from a range of 20 different types of branded beverage options (still or carbonated) from various manufacturers; to be classified as non-nutritive, the beverages selected for inclusion had to contain <5 kcal per 8oz (equivalent to 2.11 kcal per 100 mL) All participants were part of a 12-wk weight management program based on The Colorado Weigh, which included energy targets for weight loss equal to each participant’s estimated RMR and advice to gradually increase activity levels to achieve 60 min of moderate activity 6 days/wk.; - Serving Size: 330 mL; Comparator: Water: participants asked to consume ≥2 svg/d of bottled water that could be still or carbonated (additional servings could be of municipal tap water) and refrain from NNS beverage consumption. All other components of the behavioral weight loss intervention were the same as the NNS group.; Duration: 12wk; Compliance: online daily beverage logs, return of empty packaging, and periodic 24-hour dietary recall assessments; adherence NR; Outcome assessment methods and timing:; - Fasting blood samples were collected; - Baseline, 12wk | [underlined: Change in fasting plasma glucose (mmol/L)], Mean (SD); Within group: Baseline, 12wk; Water (n=100): 5.1 (0.5), 5.0 (0.4), P<0.05; NNS (n=95): 5.0 (0.5), 5.0 (0.5), P=NS; Between groups: Difference over 12wk; 0.0 (0.8), P=NS; [underlined: Change in fasting serum insulin (pmol/L)], Mean (SD); Within group: Baseline, 12wk; Water (n=94): 87.9 (75.9), 67.0 (34.8), P<0.05; NNS (n=95): 79.2 (47.6), 67.0 (48.0), P<0.05; Between groups: Difference over 12wk; -8.7 (113.3), P=NS; [underlined: Change in HbA1c (mmol/mol)], Mean (SD); Within group: Baseline, 12wk; Water (n=101): 36.7 (3.8), 35.8 (3.4), P<0.001; NNS (n=95): 36.7 (4.6), 36.5 (3.5), P=NS; Between groups: Difference over 12wk -0.7 (4.8), P<0.05 | Model adjustments:; - TEI: no; Limitations:; - High attrition rate with no information on non-completers; - Unclear if sufficiently powered; Funding:; American Beverage Association
Harrold, 2024^5^; RCT-Parallel, SWITCH Trial (The effectS of non-nutritive sWeetened beverages on appetITe during aCtive weigHt loss), UK; Baseline N=493, Analytic N=135 (Attrition: 73%, impacted by COVID-19 pandemic); Study objective: To compare the effects of non-nutritive sweetened beverages and water on body weight during weight loss and maintenance in a behavioural weight management programme; Participant characteristics at baseline: adults with overweight and obesity; - Age (mean and/or range): 45.4 (11.6)y; 18-65y; - Female: 70%; - Race and/or ethnicity: NR; - Socioeconomic position: NR; - Anthropometry: BMI 31 (2) kg/m^2^; - Physical activity: ~8550 steps/d; - Family history of diabetes: NR; - Smoking: All nonsmokers; - Alcohol intake: NR; - TEI: NR; - Beverage intake at baseline: All drink <2 L/d of NNS (inclusion criteria); 24% were NNS naïve (NNS ≤25% of drink choices in 5y before screening); Excluded from study or analysis: <18 or >65y; BMI <27 or >35 kg/m^2^; drinking chilled beverages <3/wk; first-year university student; diabetes, gastrointestinal or cardiovascular disease; bariatric surgery; medication or supplements known to affect weight; pregnant or breastfeeding; food allergies or intolerances; recent or current smokers; dieting or significant weight loss; regular intense exercise; working in appetite or feeding-related disciplines; food-avoidance diet, abnormal eating behavior, or non-breakfast eaters | Intervention: Non-nutritive sweetened beverages (NNS): ≥2 svg/d; participants could select from a range of 20 different types of branded beverage options (still or carbonated) from various manufacturers; to be classified as non-nutritive, the beverages selected for inclusion had to contain <5 kcal per 8oz (equivalent to 2.11 kcal per 100 mL) All participants were part of a 12-wk weight loss program based on The Colorado Weigh, which included energy targets for weight loss equal to each participant’s estimated RMR and advice to gradually increase activity levels to achieve 60 min of moderate activity 6 days/wk. This was followed by a 40-wk assisted weight maintenance phase.; - Serving Size: 330 mL; Comparator: Water: participants asked to consume ≥2 svg/d of bottled water that could be still or carbonated (additional servings could be of municipal tap water) and refrain from NNS beverage consumption. All other components of the weight loss/maintenance intervention were the same as the NNS group.; Duration: 12wk; Compliance: online daily beverage logs, return of empty packaging, and periodic 24-hour dietary recall assessments; adherence NR; Outcome assessment methods and timing:; - Fasting blood samples were collected; - Baseline, 52wk | [underlined: Change in fasting plasma glucose (mmol/L)], Mean (SD); Within group: Baseline, 52wk; Water (n=67): 5.1 (0.5), 5.0 (0.5), P=NS NNS (n=66): 5.0 (0.4), 5.0 (0.5), P=NS; Between groups: Difference over 52wk; 0.0 (0.8), P=NS; [underlined: Change in fasting serum insulin (pmol/L)], Mean (SD); Within group: Baseline, 52wk; Water (n=63): 87.8 (78.1), 76.1 (53.4), P=NS NNS (n=65): 77.7 (43.6), 63.6 (34.3), P<0.05; Between groups: Difference over 52wk; 2.4 (123.9), P=NS; [underlined: Change in HbA1c (mmol/mol)], Mean (SD); Within group: Baseline, 52wk; Water (n=69): 36.3 (3.7), 35.7 (3.3), P<0.05; NNS (n=66): 36.3 (3.3), 36.4 (3.2), P=NS; Between groups: Difference over 52wk; 0.8 (5.2), P=NS | Model adjustments:; - TEI: no; Limitations:; - High attrition rate with no information on noncompleters; - Unclear if sufficiently powered; Funding:; American Beverage Association
Kendig, 2023^6^; RCT-Parallel, Australia; Baseline N=118, Analytic N=80 (Attrition: 32%); Study objective: To assess the effects of a 12-week intervention in which young healthy adults who regularly consumed SSBs were instructed to replace SSB intake with artificially-sweetened beverages, water, or to continue SSB intake.; Participant characteristics at baseline: young adults that habitually consume SSB; - Age (mean and/or range): 22.9 (3.9)y; 18-35y; - Female: 40%; - Race and/or ethnicity: NR; - Socioeconomic position: NR; - Anthropometry: BMI 23.2 (3.6) kg/m^2^; - Physical activity: NR; - Family history of diabetes: NR; - Smoking: NR; - Alcohol intake: NR; - TEI: NR; - Beverage intake at baseline: NR; Excluded from study or analysis: <18 or >35y; BMI <17.5 or >30 kg/m^2^; regularly consumed less than 2 L/wk of SSB; participants with average weekly SSB intake >1.5 times their group’s IQR | Intervention: Artificially-sweetened beverages (n=28): commercially-available diet drinks sweetened with aspartame, acesulfame-K, and sucralose; - Serving Size: 4.5 L/wk (as 12 x 375mL cans and ≤3 cans/d); Comparator: Water (n=25): 4.5 L/wk as 12 x 375mL cans; Duration: 12wk; Compliance: questionnaire on weekly drink adherence and weekly SSB intake; Outcome assessment methods and timing:; - Fasting blood samples were collected and 60-min OGTT was conducted.; - Baseline (test 1), 12wk (test 3) | [underlined: Change in OGTT blood glucose (mM) over 12wk]; Water vs Artificially-sweetened beverages: Data NR (figure only), P=NS | Model adjustments:; - TEI: no; Limitations:; - Methods for randomization and concealment NR; - Concerns with deviations from intended intervention; - High attrition rate with no information on noncompleters; - Not sufficiently powered; - Trial registry did not include data analysis plan; Funding:; Australian Research Council Discovery Project
Madjd, 2015^7^; RCT-Parallel, Iran; Baseline N=71, Analytic N=62 (Attrition: 13%); Study objective: To compare the effect on weight loss of either replacing diet beverages with water or continuing to consume diet beverages in adults during a 24-wk weight-loss program; Participant characteristics at baseline: women with overweight and obesity; - Age (mean and/or range): 32 (7)y; 18-50y; - Female: 100%; - Race and/or ethnicity: NR; - Socioeconomic position: NR; - Anthropometry: BMI 33 (3) kg/m^2^; - Physical activity: NR; - Family history of diabetes: NR; - Smoking: All nonsmokers; - Alcohol intake: NR; - TEI: ~2450 kcal/d; - Beverage intake at baseline: All habitual consumers of diet beverages; amount NR; Excluded from study or analysis: <18 or >50y; BMI <27 or >40 kg/m^2^; not habitual consumers of diet beverages; cardiovascular diseases, stroke, diabetes, liver diseases, kidney diseases, depression, cancer, or autoimmune disease; smokers; pregnancy or lactation during previous 6mo or planned pregnancy in next 6mo; weight loss ≥10% of body weight within 6mo before enrollment in study; participating in a research project involving weight loss or physical activity in previous 6mo; taking medication to lower lipids/cholesterol that could affect metabolism or change body weight; heart disorders, frequent chest pains, faintness, or dizziness; unable to keep 4d food record and safely participate in daily physical activity | Intervention: Diet beverage (DB, n=32), drank once a day after lunch (5 days/wk) with water during remainder of week. Both groups consumed a hypo-energetic diet (500-1000kcal deficit based on EER) according to NovinDiet protocol, which included advice to gradually increase activity levels to achieve 60 min of moderate activity 5 days/wk.; - Serving Size: 250 mL; Comparator: Water (n=30), replaced habitual intake of diet beverages with glass of water (250 mL) after lunch; Duration: 24wk; Compliance: Biweekly visits to the dietitian were required to promote adherence to the hypoenergetic diet and beverage substitution. Beverage intake compliance NR.; Outcome assessment methods and timing:; - Fasting blood samples were collected and used to calculate HOMA-IR. Standard methods were used to collect 2-hr postprandial blood glucose (2hpp glucose).; - Baseline, 24wk | [underlined: Change in fasting plasma glucose (mmol/L)], Mean (SD); Within group: Baseline, 24wk; Water: 5.3 (0.5), 4.5 (0.5), P<0.001; DB: 5.3 (0.4), 4.6 (0.4), P<0.001 Between groups: Change over 24wk; Water: -0.767 (0.278); DB: -0.681 (0.169); P-interaction=0.143; [underlined: Change in fasting serum insulin (mU/L)], Mean (SD); Within group: Baseline, 24wk; Water: 13.6 (2.2), 10.8 (1.9), P<0.001; DB: 13 (3.3), 11.3 (2.8), P<0.001; Between groups: Change over 24wk; Water: -2.8 (0.8); DB: -1.8 (1.3); P-interaction<0.001; [underlined: Change in 2hpp glucose (mmol/L)], Mean (SD); Within group: Baseline, 24wk; Water: 6.7 (0.7), 5.7 (0.5), P<0.001; DB: 6.6 (0.6), 5.9 (0.6), P<0.001; Between groups: Change over 24wk; Water: -1.024 (0.254); DB: -0.719 (0.275); P-interaction<0.001; [underlined: Change in HOMA-IR], Mean (SD); Within group: Baseline, 24wk; Water: 3.2 (0.7), 2.2 (0.5), P<0.001; DB: 3.1 (0.8), 2.3 (0.7), P<0.001; Between groups: Change over 24wk; Water: -0.097 (0.049); DB: -0.057 (0.042); P-interaction<0.001; [underlined: Change in HbA1c (%)], Mean (SD); Within group: Baseline, 24wk; Water: 5.1 (0.4), 4.5 (0.5), P<0.001; DB: 4.9 (0.4), 4.5 (0.4), P<0.001; Between groups: Change over 24wk; Water: -0.54 (0.12); DB: -0.47 (0.17) P-interaction=0.066 | Model adjustments:; - TEI: yes (NS between-group differences at baseline); Limitations:; - Concerns with deviations from intended intervention; - Trial registry did not include data analysis plan; Funding:; School of Life Sciences, University of Nottingham, United Kingdom; Digestive Disease Research Institute affiliated with Tehran University of Medical Sciences
Madjd, 2018^8^; RCT-Parallel, Iran; Baseline N=71, Analytic N=71 (Attrition: 0%); Study objective: To evaluate effects of replacing diet beverages with water on body weight maintenance over a 53-wk period in participants who undertook a 24-wk weight loss program.; Participant characteristics at baseline: women with overweight and obesity; - Age (mean and/or range): 32 (7)y; 18-50y; - Female: 100%; - Race and/or ethnicity: NR; - Socioeconomic position: NR; - Anthropometry: BMI 33 (3) kg/m^2^; - Physical activity: NR; - Family history of diabetes: NR; - Smoking: All nonsmokers; - Alcohol intake: NR; - TEI: ~2450 kcal/d; - Beverage intake at baseline: All habitual consumers of diet beverages; amount NR; Excluded from study or analysis: <18 or >50y; BMI <27 or >40 kg/m^2^; not habitual consumers of diet beverages; cardiovascular diseases, stroke, diabetes, liver diseases, kidney diseases, depression, cancer, or autoimmune disease; smokers; pregnancy or lactation during previous 6mo or planned pregnancy in next 6mo; weight loss ≥10% of body weight within 6mo before enrollment in study; participating in a research project involving weight loss or physical activity in previous 6mo; taking medication to lower lipids/cholesterol that could affect metabolism or change body weight; heart disorders, frequent chest pains, faintness, or dizziness; unable to keep 4d food record and safely participate in daily physical activity | Intervention: Diet beverage (DB, n=36), drank once a day after lunch (5 days/wk) with water during remainder of week. Both groups consumed a hypo-energetic diet (500-1000kcal deficit based on EER) according to NovinDiet protocol, which included advice to gradually increase activity levels to achieve 60 min of moderate activity 5 days/wk.; - Serving Size: 250 mL; Comparator: Water (n=35), replaced habitual intake of diet beverages with glass of water (250 mL) after lunch; Duration: 24wk; Compliance: Adherence to intervention was assessed by dietitians, based on food, beverage, physical activity logs, and weight checks. Beverage intake compliance NR.; Outcome assessment methods and timing:; - Fasting blood samples were collected and used to calculate HOMA-IR. Standard methods were used to collect 2-hr postprandial blood glucose (2hpp glucose).; - Baseline, 24wk, 77wk | [underlined: Change in fasting plasma glucose (mmol/L)], Mean (SD); Within group: Baseline, 24wk, 77wk; Water: 5.2 (0.5), 4.6 (0.5), 4.4 (0.4), P<0.001 DB: 5.3 (0.4), 4.7 (0.4), 4.6 (0.3), P<0.001; Between groups:; Change over 12mo: P-interaction=0.018; Change over 18mo: P-interaction=0.156; [underlined: Change in fasting serum insulin (mU/L)], Mean (SD); Within group: Baseline, 24wk, 77wk; Water: 13.7 (2.1), 10.7 (2), 10.2 (2), P<0.001 DB: 13.1 (3.1), 11.4 (2.9), 11.4 (2.5), P<0.001; Between groups:; Change over 12mo: P-interaction=0.002; Change over 18mo: P-interaction<0.001; [underlined: Change in 2hpp glucose (mmol/L)], Mean (SD) Within group: Baseline, 24wk, 77wk; Water: 6.9 (0.7), 5.7 (0.5), 5.5 (0.4), P<0.001 DB: 6.7 (0.8), 5.9 (0.6), 5.9 (0.4), P<0.001; Between groups:; Change over 12mo: P-interaction<0.001; Change over 18mo: P-interaction<0.001; [underlined: Change in HOMA-IR], Mean (SD); Within group: Baseline, 24wk, 77wk; Water: 3.2 (0.6), 2.2 (0.5), 2 (0.5), P<0.001 DB: 3.1 (0.8), 2.4 (0.7), 2.3 (0.6), P<0.001; Between groups:; Change over 12mo: P-interaction=0.01; Change over 18mo: P-interaction<0.001; [underlined: Change in HbA1c (%)], Mean (SD); Within group: Baseline, 24wk, 77wk; Water: 5.1 (0.4), 4.5 (0.5), 4.4 (0.4), P<0.001; DB: 5 (0.4), 4.5 (0.4), 4.4 (0.4), P<0.001; Between groups:; Change over 12mo: P-interaction=0.07; Change over 18mo: P-interaction=0.03 | Model adjustments:; - TEI: yes (NS between-group differences at baseline); Limitations:; - Concerns with deviations from intended intervention; - Trial registry did not include data analysis plan; Funding:; School of Life Sciences, University of Nottingham, United Kingdom; Digestive Disease Research Institute affiliated with Tehran University of Medical Sciences
Peters, 2014^10^; RCT-Parallel, U.S.; Baseline N=303, Analytic N=275 (Attrition: 9%); Study objective: To compare the efficacy of non-nutritive sweetened beverages to water for weight loss during the active 12-week period of a 1-year behavioral weight loss treatment program.; Participant characteristics at baseline: adults with overweight and obesity; - Age (mean and/or range): ~47y; 21-65y; - Female: 82%; - Race and/or ethnicity: 68% White; 28% Black/African American; 2% Asian or Pacific Islander; <1% American Indian or Alaskan Native, or Multiracial Origin; 11% Hispanic/Latino; - Socioeconomic position: NR; - Anthropometry: BMI 33 (4) kg/m^2^; Weight ~93 (13)kg; - Physical activity: All <300 min/wk (inclusion criteria); ~4.35 (0.2) hr/wk of moderate physical activity; - Family history of diabetes: NR; - Smoking: NR; - Alcohol intake: NR; - TEI: NR; - Beverage intake at baseline: All drink NNS ≥3/wk; Excluded from study or analysis: <21 or >65y; BMI <27 or >40 kg/m^2^; weight change >10 pounds during past 6mo; >300 min/wk of physical activity; drinking NNS beverages <3 times/wk; women who were lactating or pregnant during previous 6mo or who were planning on becoming pregnant; individuals with diabetes, CVD, uncontrolled hypertension (as well as other diseases potentially interfering with weight loss, e.g., gastrointestinal or thyroid disease) or who used medications affecting weight and metabolism | Intervention: Non-nutritive sweetened beverages (NNS, n=142): asked to consume ≥24 fl oz/d (710 ml) of NNS beverages with unrestricted water consumption. NNS beverages were pre-mixed, commercially available, and had <5 kcal per 8oz serving. All participants were in a 12-wk behavioral weight loss treatment program, which included weekly 60min group meetings, instruction on behavioral weight loss strategies (e.g., self-monitoring, portion sizes), gradual physical activity (increase up to 60 min/d and 6 days/wk), and individualized energy targets equal to RMR to achieve weight loss of 1-2 lb/wk. Beverage content was the only difference between groups.; - Serving Size: 237 mL (8oz); Comparator: Water (n=133): asked to consume ≥24 fl oz/d (710 ml) of water and refrain from NNS beverage consumption. Instructed to not add NNS (e.g., aspartame, sucralose, stevia, diet creamers) to beverages such as coffee/tea. Foods containing NNS were permitted, but participants were not instructed to do so as part of weight loss program. All other components of the behavioral weight loss intervention were the same as the NNS group.; Duration: 12wk; Compliance: Participants recorded their daily beverage intake using paper logs; compliance was high (≥24 oz/d intake: NNS: 97%, Water: 96%; Group attendance: NNS: 91%, Water: 90%); Outcome assessment methods and timing:; - Fasting blood samples were collected; - Baseline, 12wk | [underlined: Change in fasting blood glucose (mg/dL)], Mean (SE); Within group: Baseline, 12wk; Water: 90.92 (1.47), 93.40, P=0.0193; NNS: 91.44 (1.45), 93.59 (0.95), P=0.0375; Between groups: Change over 12wk; P=0.8224 | Model adjustments:; - TEI: no; Limitations:; - No preregistered data analysis plan for secondary outcomes; Funding:; American Beverage Association
Peters, 2016^9^; RCT-Parallel, U.S.; Baseline N=303, Analytic N=221 (Attrition: 27%); Study objective: To evaluate the effects of water versus beverages sweetened with non-nutritive sweeteners on body weight in subjects enrolled in a year-long behavioral weight loss treatment program with a 12-week weight loss intervention followed by a 40-week weight loss maintenance intervention.; Participant characteristics at baseline: adults with overweight and obesity; - Age (mean and/or range): ~47y; 21-65y; - Female: 82%; - Race and/or ethnicity: 68% White; 28% Black/African American; 2% Asian or Pacific Islander; <1% American Indian or Alaskan Native, or Multiracial Origin; 11% Hispanic/Latino; - Socioeconomic position: NR; - Anthropometry: BMI 33 (4) kg/m^2^; - Physical activity: All <300 min/wk (inclusion criteria); ~4.35 (0.2) hr/wk of moderate physical activity; - Family history of diabetes: NR; - Smoking: NR; - Alcohol intake: NR; - TEI: NR; - Beverage intake at baseline: All drink NNS ≥3/wk; Excluded from study or analysis: <21 or >65y; BMI <27 or >40 kg/m^2^; weight change >10 pounds during past 6mo; >300 min/wk of physical activity; drinking NNS beverages <3 times/wk; lactating or pregnant during previous 6mo or planning on becoming pregnant; individuals with diabetes, CVD, uncontrolled hypertension (as well as other diseases potentially interfering with weight loss, e.g., gastrointestinal or thyroid disease) or who used medications affecting weight and metabolism | Intervention: Non-nutritive sweetened beverages (NNS, n=114): asked to consume ≥24 fl oz/d (710 ml) of NNS beverages with unrestricted water consumption. NNS were pre-mixed, commercially available, and <5 kcal per 8oz serving. All participants were in a 12wk behavioral weight loss treatment program, which included weekly 60min group meetings, instruction on behavioral weight loss strategies, gradual physical activity (increase up to 60 min/d and 6 days/wk), and individualized energy targets equal to RMR to achieve weight loss of 1-2 lb/wk. This was followed by a 40wk weight maintenance program, which included 9 monthly 60min group meetings, a diet of 25-35% kcal from fat, and maintenance of physical activity. Beverage content was the only difference between groups.; - Serving Size: 237 mL (8oz); Comparator: Water (n=107): asked to consume ≥24 fl oz/d (710 ml) of water and refrain from NNS beverage consumption. Instructed to not add NNS (e.g., aspartame, sucralose, stevia, diet creamers) to beverages such as coffee/tea. Foods containing NNS were permitted, but participants were not instructed to do so as part of weight loss program. All other components of the weight loss/maintenance intervention were the same as NNS group.; Duration: 52wk; Compliance: Participants recorded their daily beverage intake using paper logs; compliance was high (≥24 oz/d intake: NNS: 98%, Water: 98%; Group attendance: NNS: 85%, Water: 85%); Outcome assessment methods and timing:; - Fasting blood samples were collected; - Baseline, 52wk | [underlined: Change in fasting blood glucose (mg/dL)], Mean (SE); Within group: Baseline, 52wk; Water: 90.92 (1.39), 92.55 (1.50), P=0.127; NNS: 91.44 (1.37), 92.28 (1.46), P=0.411; Between groups: Change over 52wk; P=0.597 | Model adjustments:; - TEI: no; Limitations:; - Missing data with no information on noncompleters; - No preregistered data analysis plan for secondary outcomes; Funding:; American Beverage Association
Tate, 2012^11^; RCT-Parallel, CHOICE (Choose Healthy Options Consciously Everyday), U.S.; Baseline N=318, Analytic N=313 (Attrition: 2%); Study objective: To compare the replacement of caloric beverages with water or diet beverages as a method of weight loss over 6mo in adults and attention controls; Participant characteristics at baseline: adults with overweight and obesity; - Age (mean and/or range): 42 (10.7)y; 18-65y; - Female: 84%; - Race and/or ethnicity: 40% White; 54% Black; 6% Other; - Socioeconomic position: 52% college graduate or beyond; 39% some college; 9% high school or less; 54% married or living with partner; - Anthropometry: BMI 36.3 (5.9) kg/m^2^; - Physical activity: NR; - Family history of diabetes: NR; - Smoking: 8% current; 25% former; - Alcohol intake: NR; - TEI: ~2170 kcal/d; - Beverage intake at baseline: NR; Excluded from study or analysis: <18 or 65y; BMI <25 or >49.9 kg/m^2^; consumed <280 kcal/d of caloric beverages; recent weight loss of >5%; participation in other weight-loss or physical-activity research; lactation; recent or planned pregnancy; thyroid medication use; diabetes mellitus treated with oral medication or insulin; cancer in prior 5y; history of myocardial infarction or heart surgery; current psychiatric treatment; psychiatric hospitalization in past year; alcohol dependence; plans to move or unable to attend monthly group meetings; inadequate means to transport beverages; self-report of heart problems, frequent chest pains, or faintness or dizziness | Intervention: Diet beverages (n=105): encouraged to replace ≥2 svg/d (≥200 kcal) of caloric beverages with diet beverages (LNCSB); could choose any combination of noncaloric sweetened beverages (carbonated, noncarbonated, noncaffeinated, and caffeinated beverages) provided at monthly group meetings (4 single-serving beverages per day); - Serving Size: 355-500 mL (12-16oz); Comparator: “Attention Control” (AC, n=105): equal treatment contact time and attention involving monthly group sessions and weigh-ins, weekly monitoring, general weight-loss information (e.g., product labels, vegetable consumption, portion control, physical activity). Participants were not provided with beverages, given weight-loss or physical activity goals, or encouraged to change beverage intake (beverages were not mentioned during lessons or group sessions).; Water (n=108): encouraged to replace ≥2 svg/d (≥200 kcal) of caloric beverages with water; could choose any combination of bottled still and non-sweetened sparkling water, which were provided at monthly group meetings; Duration: 26wk; Compliance: Monthly group counseling to promote adherence; DB and Water groups attended significantly more group sessions than AC group. Two unannounced 24-h dietary recalls via telephone (one weekday and one weekend day) at each assessment period (baseline, 3mo, 6mo).; Outcome assessment methods and timing:; - Fasting blood samples were collected; - Baseline, 3mo and 6mo follow-up | [underlined: Change in fasting blood glucose (mg/dL)], Mean (95% CI); Within group: Baseline, 3mo, 6mo; Attention Control: 88.6 (86.6, 90.6); 87.5 (85.1, 89.9); 89.2 (87.2, 91.1), P=0.0058; LNCSB: 91.7 (89.3, 94.1); 90.2 (87.7, 92.7); 89.7 (87.6, 91.9), P=0.0978; Water: 93.1 (88.9, 97.2); 90.1 (85.7, 94.6); 89.9 (87.4, 92.3), P=0.0027; Between groups: Change over 6mo; Attention Control: 0.59 (0.35, 0.83); Water: -3.21 (-3.89, -2.53); LNCSB: -1.92 (-2.38, -1.46); Water vs LNCSB: Data NR (Control was REF); Attention Control vs LNCSB: P=0.1471 | Model adjustments:; - TEI: no; Limitations:; - Amount of carbonated and/or caffeinated versions of beverages was not taken into account; - Trial registry did not include data analysis plan; Funding:; Nestlé Waters USA
Viveros-Watty, 2022^12^; RCT-Parallel, Mexico; Baseline N=51, Analytic N=45 (Attrition: 12%); Study objective: To evaluate the effect of reducing consumption of artificially-sweetened beverages on the metabolism in young adults with overweight.; Participant characteristics at baseline: Young adults with overweight and obesity; - Age (mean and/or range): 21.4 (2.1)y; 19-27y; - Female: 69%; - Race and/or ethnicity: NR (Mexican); - Socioeconomic position: NR; - Anthropometry: 29% with overweight, 71% with obesity; - Physical activity: All with low-intensity physical activity (inclusion criteria); - Family history of diabetes: NR; - Smoking: NR; - Alcohol intake: NR; - TEI: 2055 (781) kcal/d; - Beverage intake at baseline: 14.1 (7.4) portions/wk of artificially-sweetened beverages; Excluded from study or analysis: <19 or >27y; BMI <25 or >35 kg/m^2^; habitual consumption of artificially-sweetened beverages <3 svg/wk; hyper-or hypothyroidism; pregnancy; those who performed moderate to high physical activity; those who ingested medication that could interfere with biochemical and anthropometric parameters; those with metabolic complications; loss to follow-up | Intervention: No artificially-sweetened beverages (No ASB, n=24): participants could not consume ASB but were allowed other beverages with no artificial sweeteners; - Serving Size: N/A; Comparator: Control (Usual ASB, n=21): usual consumption of ≥3 svg/wk (1 svg = 250 mL); Duration: 12wk; Compliance: weekly text message (intervention group message included a reminder to interrupt consumption of artificially-sweetened beverages); Outcome assessment methods and timing:; - Fasting blood samples were collected and used to calculate HOMA-IR.; - Baseline, 12wk | [underlined: Change in fasting plasma glucose (mg/dL)], Median (IQR); Within group: Baseline, 12wk; Usual ASB: 78 (74.50–88.50), 80 (78–85.50), P=0.72; No ASB: 83.50 (80.25–87), 79.50 (75–86), P=0.024; Between groups: % of change over 12wk; Usual ASB: 1.28 (-5.56–7.71); No ASB: -6.13 (-10.19–0.29); P<0.05; [underlined: Change in fasting plasma insulin (mcU/mL)], Median (IQR); Within group: Baseline, 12wk; Usual ASB: 21.36 (15.79–27.58), 28.82 (20.22– 35.02), P=0.001; No ASB: 25.59 (20.91–30.26), 22.13 (17.42–27.15),; P=0.04; Between groups: % of change over 12wk; Usual ASB: 21.38 (4.86–56.17); No ASB: -6.30 (-34.56–6.65); P=0.00005; [underlined: Change in HOMA-IR], Median (IQR); Within group: Baseline, 12wk; Usual ASB: 4.30 (3.24–5.59), 5.46 (4.05–7.16), P=0.001; No ASB: 5.36 (4.15–6.50), 4.47 (3.31–5.52), P=0.014; Between groups: % of change over 12wk; Usual ASB: 21.96 (6.40–53.9); No ASB: -14.25 (-37.20–2.18); P=0.00002 | Model adjustments:; - TEI: yes (NS between-group differences at baseline or during study); Limitations:; - Concerns with deviations from intended intervention; Funding:; CONACYT

a Abbreviations: ASB: artificially-sweetened beverage(s); BMI: body mass index; CI: confidence interval; CVD: cardiovascular disease; d: day(s); dL: deciliter(s); HbA1C: hemoglobin A1C; hr: hour; HOMA-IR: Homeostatic Model Assessment for Insulin Resistance; IAUC: incremental area under the curve; IQR: interquartile range; kcal: kilocalorie(s); kg: kilogram(s); LNCSB: low- and no-calorie sweetened beverage(s); m: meter(s); mcU: micro unit; mg: milligram(s); min: minute(s); mL: milliliter(s); N/A: not applicable; nmol: nanomole; NR: not reported; NS: not significant; OGTT: oral glucose tolerance test; oz: ounce(s); RCT: randomized controlled trial; REF: reference group; SD: standard deviation; SSB: sugar-sweetened beverage(s); svg: serving(s); T2D: type 2 diabetes; TEI: total energy intake; μmol: micromole(s); wk: week(s); y: year(s)

Table 10 Observational studies examining the relationship between low- and no-calorie sweetened beverage consumption in adults and older adults and risk of type 2 diabetes^a^

Study and Participant Characteristics | Exposure, Comparator, and Outcome(s) | Results | Methodological Considerations
Bazzano, 2008^13^; PCS, NHS (Nurses’ Health Study), U.S.; Analytic N=71,346; Study objective: To examine the association between fruit, vegetable, and fruit juice intake and development of T2D; Participant characteristics at baseline: women; - Age (mean and/or range): 50 (7)y; 38-63y; - Female: 100%; - Race and/or ethnicity: Primarily Caucasian; - Socioeconomic position: All nurses; - Anthropometry: BMI 23 (7) kg/m^2^; - Physical activity: 2 (2) hr/wk; - Family history of diabetes: 25%; - Smoking: 24% current; - Alcohol intake: 7 (11) g/d; - TEI: 1457-2061 kcal/d; - Beverage intake at baseline: NR; Excluded from study or analysis: baseline diabetes; cancer or cardiovascular disease; missing data; loss to follow-up; energy intake <600 or >3500 kcal/d | Exposure: Low-calorie cola; - Serving Size: NR; Comparator: continuous intake (svg/d); Assessment methods and timing:; - FFQ assessing usual intake during previous year.; - 1984, 1986, 1990, 1994, 1998 (cumulative average of median values from all available questionnaires up to the start of each 2y follow-up period); Outcome assessment methods and timing:; - Self-reported via biennial questionnaire; verified with supplementary questionnaire specific to T2D; - 18y | [underlined: T2D by cumulative average of median intake], HR (95% CI); Per 1 svg/d of low-calorie cola: 1.11 (1.07, 1.16) | Model adjustments:; - TEI: yes; - Key confounders: sex, age, anthropometry, physical activity, family history of diabetes, smoking, alcohol intake; - Other: postmenopausal hormone use; consumption of whole grains, nuts, processed meats, coffee, and potatoes; Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position; - No evidence whether the result was biased due to missing data; - No preregistered data analysis plan; Funding:; NIH
Bhupathiraju, 2013^14^; PCS, NHS (Nurses’ Health Study) and HPFS (Health Professionals Follow-Up Study), U.S.; Analytic N=74,749 (NHS); 39,059 (HPFS); Study objective: To prospectively examine the association of caffeinated compared with caffeine-free beverages, including coffee, tea, SSB, and carbonated artificially sweetened beverages, with T2D risk; Participant characteristics at baseline: nurses and health professionals; - Age (mean and/or range): ~50y, 38-63y (NHS); ~53y, 40-75y (HPFS); - Female: 100% (NHS), 0% (HPFS); - Race and/or ethnicity: Primarily Caucasian; - Socioeconomic position: Mainly educated health professionals; - Anthropometry: BMI ~25 kg/m^2^ in both NHS and HPFS; - Physical activity: METs/wk, ~14 (NHS); ~21 (HPFS); - Family history of diabetes: 28% NHS; 20% HPFS; - Smoking: current, 25% NHS; 9% HPFS; - Alcohol intake: ~7 g/d in NHS; ~11 g/d in HPFS; - TEI: ~1800 kcal/d in NHS; ~2000 kcal/d in HPFS; - Beverage intake at baseline: ~0.6 svg/d LNCSB in both NHS and HPFS; Excluded from study or analysis: baseline diabetes; cancer or cardiovascular disease; women who left ≥10 items blank on FFQ or energy intakes <500 or >3500 kcal/d; men who left ≥70 items blank on the FFQ or energy intake <800 or >4200 kcal/d | Exposure: Artificially-sweetened beverages (ASB, including caffeinated and caffeine-free colas and carbonated soft drinks); - Serving Size: ~355 mL (“one standard glass, can, or bottle”); Comparator: continuous intake (per 1 svg/d); categorical intake (<1/mo, 1-4/mo, 2-6/wk, ≥1/d); Assessment methods and timing:; - FFQ assessing usual intake during previous year.; - Baseline (1984 in NHS, 1986 in HPFS), and every 4y for 22-24y follow-up (until 2008 in NHS and 2008 in HPFS) - cumulative average of intake; Outcome assessment methods and timing:; - Self-reported via biennial questionnaire; verified with supplementary questionnaire specific to T2D; - Up to 2008, maximum 22y (HPFS) and 24y (NHS) | [underlined: T2D by cumulative average intake], RR (95% CI); NHS; Caffeinated ASB; <1/mo (ref); 1-4/mo: 1.02 (0.95, 1.09); 2-6/wk: 0.99 (0.92, 1.05); ≥1/d: 1.01 (0.93, 1.10); P-trend=0.99; Per-serving increment: 1.01 (0.97, 1.06); Caffeine-free ASB; <1/mo (ref); 1-4/mo: 1.00 (0.93, 1.07); 2-6/wk: 1.02 (0.95, 1.09); ≥1/d: 1.09 (1.00, 1.18); P-trend=0.02; Per-serving increment: 1.06 (1.03, 1.10); HPFS; Caffeinated ASB; <1/mo (ref); 1-4/mo: 1.03 (0.92, 1.15); 2-6/wk: 0.97 (0.87, 1.09); ≥1/d: 1.06 (0.93, 1.22); P-trend=0.55; Per-serving increment: 0.98 (0.91, 1.04); Caffeine-free ASB; <1/mo (ref); 1-4/mo: 1.02 (0.91, 1.14); 2-6/wk: 1.04 (0.93, 1.16); ≥1/d: 1.15 (0.99, 1.33); P-trend=0.06; Per-serving increment: 1.06 (0.99, 1.14); No significant interaction between beverage intake and BMI, physical activity, or smoking (data not shown). | Model adjustments:; - TEI: yes; - Key confounders: sex, age, anthropometry, physical activity, family history of diabetes, smoking, alcohol intake; - Other: postmenopausal hormone use (NHS), alternative HEI, and consumption of other beverages other than the main exposure, depending on model, presence of hypertension, hypercholesterolemia, adherence to low-calorie diet; Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position; - No evidence whether the result was biased due to missing data; - No preregistered data analysis plan; Funding:; NIH
Chen, 2023^15^; PCS, NHS (Nurses’ Health Study), NHS-II, HPFS (Health Professionals Follow-Up Study), U.S.; Analytic N=198,636 (71,871 in NHS; 87,918 in NHS-II; 38,847 in HPFS); Study objective: To examine the relationship between ultra-processed food intake and T2D risk among 3 large U.S. cohorts; Participant characteristics at baseline: nurses and health professionals; - Age (mean and/or range): ~50y, 38-63y (NHS); ~36y, 27-44y (NHS-II); ~52y, 40-75y (HPFS); - Female: 80%; - Race and/or ethnicity: Primarily Caucasian; - Socioeconomic position: Mainly educated health professionals; - Anthropometry: BMI ~26 kg/m^2^; - Physical activity: MET-hr/wk, ~26 (NHS); ~18 (NHS-II); ~34 (HPFS); - Family history of diabetes: 27% NHS; 33% NHS-II; 14% HPFS; - Smoking: current, 10% NHS; 9% NHS-II; 6% HPFS; - Alcohol intake: ~5.5 g/d (NHS); ~3.5 g/d (NHS-II); ~10.5 g/d (HPFS); - TEI: ~1800 kcal/d (NHS and NHS-II); ~2000 kcal/d (HPFS); - Beverage intake at baseline: 0.6 (0.8) svg/d of ASB; Excluded from study or analysis: baseline diabetes; cancer or cardiovascular disease; missing data; loss to follow-up; energy intake <500 or >3500 kcal/d for women, <800 or >4200 kcal/d for men | Exposure: Artificially-sweetened beverages (caffeinated, caffeine-free, carbonated and noncarbonated low- calorie soda; other low-calorie Cola with caffeine); - Serving Size: NR; Comparator: continuous intake (per 1 svg/d increase); Assessment methods and timing:; - FFQ assessing usual intake during previous year.; - Baseline (1984 in NHS, 1986 in HPFS, 1991 in NHS-II), and every 4y until 2016 in NHS and HPFS and until 2017 in NHS-II; Outcome assessment methods and timing:; - Self-reported via biennial questionnaire; verified with supplementary questionnaire specific to T2D; - Up to 2016 in NHS and HPFS, and up to 2017 in NHS-II | [underlined: T2D by cumulative average intake], HR (95% CI); Per 1 svg/d increase: 1.09 (1.08, 1.11) | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position (neighborhood income), anthropometry, physical activity, family history of diabetes, smoking, alcohol intake; - Other: physical examination; menopausal status (NHS-II); postmenopausal hormone use (NHS and NHS-II); oral contraceptive use (NHS-II); history of hypercholesterolemia and hypertension; other ultra-processed food subgroups; Limitations:; - No evidence whether the result was biased due to missing data; - No preregistered data analysis plan; Funding:; NIH
de Koning, 2011^16^; PCS, HPFS (Health Professionals Follow-Up Study), U.S.; Analytic N=41,109; Study objective: To examine the associations of SSB and ASB with incident T2D; Participant characteristics at baseline: male health professionals; - Age (mean and/or range): 51y; 40-75y; - Female: 0%; - Race and/or ethnicity: Primarily Caucasian; - Socioeconomic position: All health professionals; - Anthropometry: BMI ~25.5 (3.2) kg/m^2^; - Physical activity: ~21 METs/wk; - Family history of diabetes: 12%; - Smoking: 9% current; - Alcohol intake: ~11 g/d; - TEI: ~1950 kcal/d; - Beverage intake at baseline: 0.49 (0.94) svg/d of LNCSB; Excluded from study or analysis: baseline diabetes; <40 or >75y at recruitment, T1D, cardiovascular disease (heart attack, stroke, angina, coronary artery bypass graft), cancer (except melanoma skin cancer), energy intake <800 or >4299 kcal/d | Exposure: Artificially sweetened beverages (caffeinated, caffeine-free, and noncarbonated low-calorie beverages); - Serving Size: 1 svg = “one standard glass, can, or bottle”; Comparator: continuous intake (per 1 svg/d); categorical intake (quartiles); - Quartile 1: never; - Quartile 2: 2/mo; - Quartile 3: 1-4/wk; - Quartile 4: 4.5/wk to 18/d; Assessment methods and timing:; - FFQ assessing usual intake during previous year.; - Baseline, and every 4y for 20y; Outcome assessment methods and timing:; - Self-reported via biennial questionnaire; verified with supplementary questionnaire specific to T2D; - 20y | [underlined: T2D by cumulative average intake], HR (95% CI); Q1: REF; Q2: 1.09 (0.96, 1.24); Q3: 0.98 (0.88, 1.09); Q4: 1.09 (0.98, 1.21); P-trend=0.13; By 1 svg/d increase: 1.03 (0.99, 1.08); P=0.12; By baseline intake; Q1: REF; Q4: 1.08 (0.98, 1.19); P-trend=0.12; No significant interactions between beverage intake and age, alcohol, physical activity, or family history (data not shown). | Model adjustments:; - TEI: yes; - Key confounders: sex, age, anthropometry, physical activity, family history of diabetes, smoking, alcohol intake; - Other: multivitamin use, high triglycerides, high blood pressure, use of diuretics, previous weight change and low-calorie diet, alternative HEI; Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position; - No evidence whether the result was biased due to missing data; - No preregistered data analysis plan; Funding:; NIH; Canadian Institutes of Health Research; Canadian Diabetes Association
Drouin-Chartier, 2019^17^; PCS, NHS (Nurses’ Health Study), NHS-II, HPFS (Health Professionals Follow-Up Study), U.S.; Analytic N=192,352 (76,531 in NHS; 81,597 in NHS-II; 34,224 in HPFS); Study objective: To evaluate the associations of long-term changes in consumption of SSB and ASB with subsequent risk of T2D; Participant characteristics at baseline: nurses and health professionals; - Age (mean and/or range): ~58y, 52-77y (NHS); ~41y, 37-54y (NHS-II); ~57y, 54-89y (HPFS); - Female: 82%; - Race and/or ethnicity: Primarily Caucasian; - Socioeconomic position: Mainly educated health professionals; - Anthropometry: BMI ~25 kg/m^2^; - Physical activity: MET-hr/wk, ~15 (NHS); ~24 (NHS-II); ~20 (HPFS); - Family history of diabetes: 28% NHS; 34% NHS-II; 26% HPFS; - Smoking: current, 19% NHS; 11% NHS-II; 8% HPFS; - Alcohol intake: NR; - TEI: ~1700 kcal/d (NHS and NHS-II); ~2000 kcal/d (HPFS); - Beverage intake at baseline: ~0.8 svg/d (NHS); ~1.5 svg/d (NHS-II); ~0.7 svg/d (HPFS); Excluded from study or analysis: baseline diabetes; cancer or cardiovascular disease; missing data; loss to follow-up; energy intake <500 or >3500 kcal/d for women, <800 or >4200 kcal/d for men | Exposure: Artificially-sweetened beverages (low-calorie beverages with or without caffeine); - Serving Size: 8oz (converted for analysis from one 12-oz glass, bottle, or can); Comparator: categorical intake (change in beverage intake); - Decrease in consumption >0.50 svg/d; - Decrease in consumption >0.07-0.50 svg/d; - No change or relatively stable consumption (±0.07 svg/d); - Increase in consumption >0.07-0.50 svg/d; - Increase in consumption >0.50 svg/d; - <1 svg/wk; - ≥1 svg/wk to <1 svg/d; - ≥1 svg/d; Assessment methods and timing:; - FFQ assessing usual intake during previous year.; - Baseline (1990 in NHS and HPFS, 1995 in NHS-II), and every 4y for up to 26y follow-up (analyzed 4y change in beverage intake on risk of T2D in the subsequent 4y period); Outcome assessment methods and timing:; - Self-reported via biennial questionnaire; verified with supplementary questionnaire specific to T2D; - Up to 2012 in NHS and HPFS, and up to 2013 in NHS-II | [underlined: T2D by 4y change in intake], HR (95% CI); Pooled (all cohorts); Decrease >0.50 svg/d: 1.05 (0.94, 1.17); Decrease >0.07-0.50 svg/d: 1.00 (0.95, 1.04); No change: REF; Increase >0.07-0.50 svg/d: 1.03 (0.95, 1.13); Increase >0.50 svg/d: 1.18 (1.02, 1.36); P-trend=0.001; By initial and final consumption of LNCSB, HR (95% CI); <1 svg/wk for 4y: REF; ≥1 svg/wk to <1 svg/d or ≥1 svg/d for 4y: higher risk, (data NR, figure only); Stratified analysis of pooled results also provided by initial AHEI index, obesity, and physical activity – no significant interactions; NHS; Decrease >0.50 svg/d: 1.10 (0.94, 1.28); Decrease >0.07-0.50 svg/d: 1.04 (0.98, 1.11); No change: REF; Increase >0.07-0.50 svg/d: 0.97 (0.86, 1.09); Increase >0.50 svg/d: 1.02 (0.83, 1.25); P-trend=0.007; NHS-II; Decrease >0.50 svg/d: 1.05 (0.86, 1.28); Decrease >0.07-0.50 svg/d: 0.96 (0.88, 1.04); No change: REF; Increase >0.07-0.50 svg/d: 1.11 (0.94, 1.30); Increase >0.50 svg/d: 1.35 (1.04, 1.76); P-trend=0.48; HPFS; Decrease >0.50 svg/d: 0.93 (0.72, 1.21); Decrease >0.07-0.50 svg/d: 0.96 (0.86, 1.07); No change: REF; Increase >0.07-0.50 svg/d: 1.11 (0.92, 1.34); Increase >0.50 svg/d: 1.38 (0.98, 1.93); P-trend=0.008 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, anthropometry, physical activity, family history of diabetes, smoking, alcohol intake; - Other: physical examination; menopausal status; postmenopausal hormone use; oral contraceptive use; AHEI score; intake of other beverages; Limitations:; - Did not account for key confounders: socioeconomic position; - No evidence whether the result was biased due to missing data; - No preregistered data analysis plan; Funding:; NIH
Fagherazzi, 2013^18^; PCS, EPIC-E3N (Etude Epidémiologique auprès de femmes de la Mutuelle Générale de l’Education Nationale), France; Analytic N=66,118; Study objective: To evaluate the association between self-reported SSB, ASB, and 100% fruit juice consumption and T2D risk over 14y of follow-up; Participant characteristics at baseline: French women; - Age (mean and/or range): 52.6 (6.6)y; - Female: 100%; - Race and/or ethnicity: NR; - Socioeconomic position: 86% graduate/postgraduate education; 14% undergraduate education; - Anthropometry: 16% with overweight, 3% with obesity; - Physical activity: 54.8 (30.2) MET-hr/wk; - Family history of diabetes: 10%; - Smoking: NR; - Alcohol intake: 11.1 (14.1) g/d; - TEI: 2170.5 (574.5) kcal/d; - Beverage intake at baseline: 567.7 (906.5) mL/wk of LNCSB; 81% non-consumers; Excluded from study or analysis: baseline diabetes; missing data; extreme energy intake (lowest and highest 1% of cohort) | Exposure: Artificially-sweetened beverages; - Serving Size: NR; Comparator: categorical intake (nonconsumers, <99 mL/wk, 99-221 mL/wk, 222-603 mL/wk, >603 mL/wk); Assessment methods and timing:; - Validated diet history questionnaire assessing usual intake during previous year.; - Baseline (1993); Outcome assessment methods and timing:; - Self-report in ≥1 of 8 questionnaires (validated with drug reimbursement claims or by self-reported questionnaire of biomarker concentrations); - Every 2-3y (mean follow-up: 14y (1993-2007)) | [underlined: T2D by baseline intake], HR (95% CI) Nonconsumers (n=53,538): REF; <99 mL/wk (n=10,856): 1.19 (1.03, 1.37); 99-121 mL/wk (n=574): 1.25 (0.77, 2.01); 222-603 mL/wk (n=575): 1.27 (0.81, 1.98); >603 mL/wk (n=575): 1.68 (1.19, 2.39); P-trend=0.0057; Stratified by BMI categories:; Nonconsumers (REF) vs >603 mL/wk; BMI <25 kg/m^2^ (n=53,695): 2.23 (1.14, 4.36); BMI between 25-30 (n=10,290): 2.17 (1.27, 3.68); BMI >30 (n=2133): 1.00 (0.52, 1.92) | Model adjustments:; - TEI: yes; - Key confounders: sex, age, socioeconomic position (years of education), anthropometry, physical activity, family history of diabetes, smoking, alcohol intake; - Other: hypertension, hypercholesterolemia, hormone replacement therapy, antidiabetic drugs, omega-3 fatty acid intake, carbohydrate intake, coffee, fruit and vegetables, processed meat consumption, dietary pattern (Western or Mediterranean); Limitations:; - Did not account for key confounders: race and/or ethnicity; - Exposure only assessed at baseline; - High attrition rate/missing data with no evidence whether the result was biased due to missing data; - No preregistered data analysis plan; Funding:; Institut National du Cancer; Mutuelle Générale de l’Education Nationale; Institut de Cancérologie Gustave Roussy;; Institut National de la Santé et de la Recherche Médicale;; European Union InterAct project
Gardener, 2018^19^; PCS, NOMAS (Northern Manhattan Study), U.S.; Analytic N=2,019; Study objective: To examine the relation between diet soda and regular soda consumption with the risk of incident diabetes in a longitudinal multiethnic population-based cohort; Participant characteristics at baseline: adults; - Age (mean and/or range): 69 (10y); ≥40y; - Female: 64%; - Race and/or ethnicity: 23% White; 22% Black; 2% Other; 53% Hispanic; - Socioeconomic position: NR; - Anthropometry: BMI 28 (5) kg/m^2^; - Physical activity: 10% moderate-heavy physical activity; - Family history of diabetes: NR; - Smoking: 17% current; 35% former; 48% never; - Alcohol intake: 36% moderate alcohol use; - TEI: 1569 (654) kcal/d; - Beverage intake at baseline: 5% drink diet soda ≥1/d; 80% drink diet soda <1/mo; Excluded from study or analysis: baseline diabetes, stroke, <40y, resided in Northern Manhattan <3mo, no telephone in household, missing data, energy intake <500 or >4000 kcal/d | Exposure: Diet soda; - Serving Size: NR; Comparator: continuous intake (number of diet sodas per day); categorical intake (<1/mo (ref), 1/mo to 6/wk, daily (≥1/d)); Assessment methods and timing:; - FFQ assessing usual intake during previous year.; - Baseline; Outcome assessment methods and timing:; - Self-report of diagnosis with diabetes or high blood sugar, or use of insulin or oral hypoglycemic medications; confirmed by medical record review.; - 11 (5)y | [underlined: T2D by baseline intake], HR (95% CI); By number of diet sodas per day Adjusted for BMI: 1.11 (0.90, 1.36); Adjusted for waist-to-hip ratio: 1.24 (1.02, 1.50); Among those with BMI <25: 0.39 (0.05, 3.12); Among those with BMI ≥25: 1.18 (0.97, 1.45); By categories of diet soda consumption Adjusted for BMI; <1/mo: REF; 1/mo to 6/wk: 1.05 (0.77, 1.43); Daily: 1.44 (0.93, 2.24); Adjusted for waist-to-hip ratio; <1/mo: REF; 1/mo to 6/wk: 1.13 (0.83, 1.56) Daily: 1.81 (1.17, 2.81); Among those with BMI <25 kg/m^2^; <1/mo: REF; 1/mo to 6/wk: 1.39 (0.56, 3.43); Daily: Model did not converge due to limited sample size; Among those with BMI ≥25 kg/m^2^; <1/mo: REF; 1/mo to 6/wk: 1.02 (0.73, 1.41); Daily: 1.63 (1.04, 2.55) | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, anthropometry, physical activity, smoking, alcohol intake; - Other: Mediterranean diet, hypertension, hypercholesterolemia; Limitations:; - Did not account for key confounders: socioeconomic position, family history of diabetes; - Exposure only assessed at baseline; - High attrition rate/missing data with no evidence whether the result was biased due to missing data; - No preregistered data analysis plan; Funding:; NIH/NINDS
Hirahatake, 2019^20^; PCS, CARDIA (Coronary Artery Risk Development in Young Adults Study), U.S.; Analytic N=4,719; Study objective: To examine the association between ASB, SSB, and total sweetened beverage consumption and T2D risk in young adults.; Participant characteristics at baseline: Black and White adults; - Age (mean and/or range): 25 (3)y; 18-30y; - Female: 55%; - Race and/or ethnicity: 50% White; 50% Black; - Socioeconomic position: ~15y education attained through follow-up; - Anthropometry: BMI 24 (5) kg/m^2^; - Physical activity: ~200 min/wk of moderate-intensity activity; - Family history of diabetes: 16%; - Smoking: 29% current; 13% former; 58% never; - Alcohol intake: ~12 mL/d; - TEI: ~2700 kcal/d; - Beverage intake at baseline: 15% drink ASB ≥1 svg/d; mean intake: 0.46 (1.0) svg/d; Excluded from study or analysis: baseline diabetes; missing data; loss to follow-up; energy intake <600 kcal or >6000 kcal/d for women, <800 or >8000 kcal/d for men | Exposure: Soft drinks and fruit drinks sweetened with non-nutritive (non-caloric) sweeteners; - Serving Size: 8oz; Comparator: continuous intake (svg/d); categorical intake (none, any to <4 svg/wk, 4 to <7 svg/wk, 1-2 svg/d, >2 svg/d; quintiles); Assessment methods and timing:; - Validated diet history questionnaire on diet during previous month. A cumulative average intake value was calculated for each participant based on dietary data collected at different time points.; - Baseline, 7y and 20y follow-up; Outcome assessment methods and timing:; - Biomarkers; - 25.3 (8.3)y (years 0, 7, 10, 15, 20, 25, 30) | [underlined: T2D by cumulative average intake], HR (95% CI); None (n=2385): REF; Any to ≤4/wk (n=1284): 0.92 (0.76, 1.12); 4 to ≤7/wk (n=361): 1.12 (0.82, 1.52); 1-2/d (n=378): 1.04 (0.75, 1.44); ≤2/d (n=311): 1.26 (0.90, 1.78); Quintile 1: REF; Quintile 2: 0.96 (0.75, 1.23); Quintile 3: 0.91 (0.71, 1.17); Quintile 4: 0.98 (0.76, 1.28); Quintile 5: 1.22 (0.92, 1.60); Per svg/d: 1.04 (0.97, 1.12), P=0.30; Results were also consistent in the subset of population with data on family history of diabetes (data NR); Stratified analyses:; Men: 1.04 (0.93, 1.16); Women: 1.06 (0.96, 1.18); P-interaction (sex)=0.90; Black: 1.16 (1.03, 1.32); White: 1.00 (0.91, 1.10); P-interaction (race)=0.13; BMI ≤ 24.9 kg/m^2^: 1.09 (0.89, 1.35); BMI 25.0-29.9 kg/m^2^: 1.11 (0.95, 1.30); BMI ≥30 kg/m^2^: 0.99 (0.90, 1.10); P-interaction (BMI)=0.72 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position (time-updated measures of education), anthropometry, physical activity, family history of diabetes, smoking, alcohol intake; - Other: CARDIA center, other beverage intake, dieting behavior, average alternate Mediterranean diet score; Limitations:; - No evidence whether the result was biased due to missing data; - No preregistered data analysis plan; Funding:; NHLBI
Huang, 2017^21^; PCS, Women’s Health Initiative, U.S.; Analytic N=64,850; Study objective: To evaluate the associations of ASB and SSB consumption with the risk of developing T2D and the potential benefit of replacing SSBs with ASBs or water.; Participant characteristics at baseline: postmenopausal women; - Age (mean and/or range): ~63y; 50-79y; - Female: 100%; - Race and/or ethnicity: 87% Non-Hispanic White; 6% African American; 4% Other; 3% Hispanic/Latino; - Socioeconomic position: 28% ≤high school, 27% some college or associate degree, 45% college or higher; 11% with annual family income <$20k, 38% with $20k<$50k, and 45% with ≥$50k (6% missing income data); 2% no health insurance; - Anthropometry: BMI ~27 (5) kg/m^2^; 36% with overweight, 24% with obesity; - Physical activity: 19% <1.8 MET hr/wk, 55% 1.8-20 MET hr/wk, 26% >20 MET hr/wk; - Family history of diabetes: 30%; - Smoking: 4% current; 44% former; 52% never; - Alcohol intake: ~5.7 g/d; - TEI: ~2300 kcal/d; - Beverage intake at baseline: LNCSB consumption: 65%, <3 svg/mo; 23%, 1-6 svg/wk; 8%, 1 svg/d; 5%, >1 svg/d; Excluded from study or analysis: baseline diabetes; missing data; BMI <18.5 kg/m^2^, energy intake <600 or >5000 kcal/d | Exposure: Artificially-sweetened beverages (diet soda and diet fruit drinks); - Serving Size: 355mL (one 12oz can); Comparator: continuous intake (every 12oz increase); categorical intake (never or <3 svg/mo, 1-6 svg/wk, 1 svg/d, ≥2 svg/d); Assessment methods and timing:; - Questionnaire on intake during the past 3 months.; - Baseline; Outcome assessment methods and timing:; - Self-report: answered yes when asked if “a doctor prescribed for the first time any of the following pills or treatments: pills for diabetes or insulin shots for diabetes”; validated by medical record review and laboratory data; - 8.4y (annually) | [underlined: T2D by baseline intake], HR (95% CI) Per 12oz increase: 1.07 (1.03, 1.11); Never or <3 svg/mo (n=42,257): REF 1-6 svg/wk (n=14,602): 1.03 (0.96, 1.11) 1 svg/d (n=4961): 1.24 (1.13, 1.37) ≥2 svg/d (n=3030): 1.21 (1.08, 1.36) P-trend<0.0001; Stratified by BMI categories BMI 18.5 to <25.0 kg/m^2^ (n=26,163); Never or <3 svg/mo: REF; 1-6 svg/wk: 0.98 (0.82, 1.16); 1 svg/d: 1.13 (0.86, 1.49); ≥2 svg/d: 1.21 (0.83, 1.78); P-trend: 0.2359; BMI 25.0 to <30.0 kg/m^2^ (n=22,994); Never or <3 svg/mo: REF; 1-6 svg/wk: 1.03 (0.91, 1.16); 1 svg/d: 1.24 (1.05, 1.48); ≥2 svg/d: 1.01 (0.80, 1.28); P-trend: 0.5649; BMI ≥30.0 kg/m^2^ (n=15,693); Never or <3 svg/mo: REF; 1-6 svg/wk: 1.02 (0.92, 1.13); 1 svg/d: 1.24 (1.08, 1.41); ≥2 svg/d: 1.26 (1.09, 1.46); P-trend: 0.0002 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position (family income; education; insurance status), anthropometry, physical activity, family history of diabetes, smoking, alcohol intake; - Other: systolic blood pressure, antihypertensive use, antihyperlipidemic use, hormone replacement therapy use, other beverage consumption, glycemic load and index, AHEI, cardiovascular history, hysterectomy history, sitting time; Limitations:; - Exposure only assessed at baseline; - High attrition rate/missing data; - No preregistered data analysis plan; Funding:; NHLBI
Imamura, 2019^22^; PCS, EPIC-InterAct, 8 European countries (France, Italy, Spain, UK, The Netherlands, Germany, Sweden, and Denmark); Analytic N=22,912; Study objective: To estimate the risk of T2D when consumption of SSB was replaced with consumption of fruit juice, milk, coffee, or tea.; Participant characteristics at baseline: adults; - Age (mean and/or range): ~54y; - Female: 58%; - Race and/or ethnicity: NR; - Socioeconomic position: 18% >high school education; 50% currently employed; - Anthropometry: BMI ~28 kg/m^2^; - Physical activity: 42% ≥moderately active; - Family history of diabetes: 30%; - Smoking: 28% current; - Alcohol intake: ~210 mL/d; - TEI: ~2150 (715) kcal/d; - Beverage intake at baseline: 24 (98) g/d of ASB; 2% consume ≥250 g/day of SSB; Excluded from study or analysis: baseline diabetes; missing data | Exposure: Artificially-sweetened beverages (carbonated/soft/isotonic drinks, diluted syrups, artificially sweetened or unsweetened, containing <2g carbohydrates/100g); - Serving Size: NR; Comparator: continuous intake (per 250 g/d); Assessment methods and timing:; - FFQ or dietary questionnaire (country-specific) assessing usual intake during previous year.; - Baseline; Outcome assessment methods and timing:; - Combination of self-report, linkage to registries, hospital/mortality data; - Median 6y | [underlined: T2D by baseline intake], HR (95% CI) Per 250 g/d: 1.01 (0.85, 1.20) | Model adjustments:; - TEI: yes; - Key confounders: sex, age, socioeconomic position (education, marital status), anthropometry, physical activity, family history of diabetes, smoking, alcohol intake; - Other: research center, hormone replacement therapy, menopausal status, history of oral contraceptive use, hypertension, dyslipidemia, coronary heart disease, stroke, dietary supplement use, dietary consumption (vegetables, fruit, nuts, cheese, yogurt, red meats, processed meats, fish, confectionary, cereals, other beverages); Limitations:; - Did not account for key confounders: race and/or ethnicity; - Exposure only assessed at baseline; - No evidence whether the result was biased due to missing data; - No preregistered data analysis plan; Funding:; EU FP6 Programme
Jensen, 2020^24^; PCS, Strong Heart Family Study, U.S.; Analytic N=1,142; Study objective: To assess the associations of diet soda and non-caloric artificial sweeteners consumption with early markers of insulin and glucose homeostasis (cross-sectionally) and incident diabetes (over an average of 8 years of follow-up) among American Indians; Participant characteristics at baseline: American Indian adults; - Age (mean and/or range): 42y; ≥18y; - Female: 62%; - Race and/or ethnicity: All American Indian; - Socioeconomic position: 62% ≤HS graduate, 24% some college, 12% ≥college degree; - Anthropometry: 28% with overweight, 50% with obesity; - Physical activity: 41% <5000 steps/d; - Family history of diabetes: NR; - Smoking: 37% current; 23% former; 38% never; - Alcohol intake: NR; - TEI: ~2300 kcal/d; - Beverage intake at baseline: 40% drink diet soda ≤1/wk, 17% 1-2 d/wk, 10% 3-6d/wk, 13% everyday; 41% reported using NAS to sweeten their beverages (20% occasionally; 8% often; 12% always); Excluded from study or analysis: baseline diabetes; CVD; missing data, energy intake <600 or >6000 kcal/d (women), or <600 or >8000 kcal/d (men) | Exposure: Diet soda (including diet drinks like Diet Coke); the use of non-caloric artificial sweeteners (NAS) to sweeten drinks; - Serving Size: NR; Comparator: dichotomous intake (any vs none); categorical intake (none, 1- 2d/wk, 3-6 d/wk, 7 d/wk); Assessment methods and timing:; - FFQ assessing usual intake during previous year and 3 additional questions on consumption frequency of diet drinks, frequency of NAS to sweeten drinks, and type of artificial sweetener used; - Baseline (2007-2009); Outcome assessment methods and timing:; - Self-report and confirmed by medical records; - 8y | [underlined: T2D by baseline intake], HR (95% CI); Diet soda; No diet soda: REF; Any diet soda: 1.74 (1.11, 2.75) P=0.02 (NS*); None: REF; 1-2 d/wk: 1.71 (0.94, 3.12), P=0.08; 3-6 d/wk: 2.22 (1.19, 4.16), P=0.01; 7 d/wk: 1.41 (0.7, 2.8), P=0.33; P-trend=0.06; Supplemental NAS to sweeten drinks; No NAS: REF; NAS: 1.68 (1.05, 2.69); P=0.03 (NS*); None: REF; Occasionally: 1.54 (0.86, 2.78), P=0.15; Often: 1.85 (0.9, 3.81), P=0.09; Always: 1.79 (0.93, 3.44), P=0.08; P-trend=0.03 (NS*); *Significance was evaluated at P<0.01 threshold to account for multiple comparisons | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position (education), anthropometry, physical activity, smoking; - Other: study site, quality of life, % of total calories from saturated fat, fruit and vegetables svg/d, processed meat svg/d, total fiber, SSB; Limitations:; - Did not account for key confounders: family history of diabetes, alcohol intake; - Exposure only assessed at baseline; - High attrition rate/missing data with no evidence whether the result was biased due to missing data; - No preregistered data analysis plan; Funding:; NIH
McNaughton, 2008^25^; PCS, Whitehall-II, UK; Analytic N=6,699; Study objective: To identify a dietary pattern associated with insulin resistance and investigate whether this pattern was prospectively associated with T2D; Participant characteristics at baseline: adults; - Age (mean and/or range): 49.5 (0.1)y; 3963y; - Female: 30%; - Race and/or ethnicity: 90% Caucasian; - Socioeconomic position: 16% low employment grade (out of 6 levels); - Anthropometry: BMI 25.3 (0.0) kg/m^2^; - Physical activity: vigorous activity 1.1 (0.0) times/wk; - Family history of diabetes: NR; - Smoking: 14% current; - Alcohol intake: 12.1 (0.2) g/d; - TEI: NR; - Beverage intake at baseline: ~22 g/d LNCSB; Excluded from study or analysis: baseline diabetes; missing data; loss to follow-up | Exposure: Low calorie/diet soft drinks dietary patterns factor identified from RRR; - Serving Size: NR; Comparator: categorical intake (based on quartiles of overall dietary pattern score) LNCSB intake (g/d), Mean (SE):; - Quartile 1: 12.5 (0.8); - Quartile 2: 18.3 (1.0); - Quartile 3: 23.5 (1.2); - Quartile 4: 73.6 (3.6); Assessment methods and timing:; - FFQ assessing usual intake during previous year.; - Baseline (1993); Outcome assessment methods and timing:; - Self-report based on doctor’s diagnosis or diabetic medication; confirmed with 2hr OGTT; - 11.6y (Phases 5 (1996-1997) and 7 (2004)) | [underlined: T2D by baseline intake], HR (95% CI) By quartiles of LNCSB intake: Data not shown P-trend=NS | Model adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position (employment grade), anthropometry, physical activity, smoking, alcohol intake; - Other: blood pressure, energy misreporting (ratio of total energy intake to energy expenditure, 1 or <1); Limitations:; - Did not account for key confounders: family history of diabetes; - Exposure subject to measurement error and only assessed at baseline; - High attrition rate/missing data with no evidence whether the result was biased due to missing data; - No preregistered data analysis plan; Funding:; UK Medical Research Council; British Heart Foundation; Health and Safety Executive (UK); Department of Health; NHLBI;; NIA; Agency for Health Care Policy Research; MacArthur Foundation Research Network on Socio-economic Status and Health
Nettleton, 2009^26^; PCS, MESA (Multi-Ethnic Study of Atherosclerosis), U.S.; Analytic N=5,011; Study objective: To determine associations between diet soda consumption and risk of incident metabolic syndrome, its components, and T2D; Participant characteristics at baseline: adults; - Age (mean and/or range): ~61y; 45-84y; - Female: 53%; - Race and/or ethnicity: 43% White; 23% African American; 12% Chinese; 21% Hispanic; - Socioeconomic position: 85% high school degree; - Anthropometry: BMI 27.9 kg/m^2^; - Physical activity: ~2400 MET-min/wk; - Family history of diabetes: NR; - Smoking: 14% current; - Alcohol intake: NR; - TEI: ~1700 kcal/d; - Beverage intake at baseline: 15% drink diet soda ≥1 svg/d; 59% never drink diet soda; Excluded from study or analysis: baseline diabetes; insufficient or implausible dietary information | Exposure: Diet soda (“diet soft drinks, unsweetened mineral water”); - Serving Size: small, medium, or large (weighted as intake frequency x 0.5, x 1.0, and x 1.5 for small, medium, and large, respectively); Comparator: categorical intake (Rare/never, >Rare/never but <1 svg/wk, ≥1 svg/wk to <1 svg/d, ≥1 svg/d); Assessment methods and timing:; - FFQ assessing usual intake during previous year.; - Baseline; Outcome assessment methods and timing:; - Self-report, fasting glucose ≥126 mg/dl at any exam, or use of antidiabetes medication; - 5.8y (baseline at 2000-2002 and 3 follow-up exams conducted from 2002-2003, 2004-2005, and 20052007) | [underlined: T2D by baseline intake], HR (95% CI); Rare/never (n=2961): REF; >Rare/never but <1 svg/wk (n=455): 0.98; (0.68, 1.42); ≥1 svg/wk to <1 svg/d (n=914): 1.25 (0.96, 1.62); ≥1 svg/d (n=681): 1.38 (1.04, 1.82); P-trend=0.01; In participants who did not consume sugarsweetened soda (n=2245); Rare/never: REF; >Rare/never but <1 svg/wk: 1.43 (0.79, 2.61); ≥1 svg/wk to <1 svg/d: 1.76 (1.18, 2.63); ≥1 svg/d: 2.23 (1.49, 3.34) | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position (education), anthropometry, physical activity, smoking; - Other: dietary supplement use; Limitations:; - Did not account for key confounders: family history of diabetes, alcohol intake; - Exposure subject to measurement error and only assessed at baseline; - High attrition rate/missing data with no evidence whether the result was biased due to missing data; - No preregistered data analysis plan; Funding:; NHLBI
O’Connor, 2016^27^; PCS, EPIC-Norfolk, UK; Analytic N=24,653; Study objective: To evaluate the association of types of SSB, ASB, and fruit juice with incident T2D; Participant characteristics at baseline: adults; - Age (mean and/or range): 58.7 (9.3)y; 4079; - Female: 55%; - Race and/or ethnicity: Primarily White European; - Socioeconomic position: 13% university degree; 44% professional or managerial social class; - Anthropometry: BMI 26.3 (3.9) kg/m^2^; 45% with overweight, 15% with obesity; - Physical activity: 18% active (based on 4level index); - Family history of diabetes: 13%; - Smoking: 12% current; - Alcohol intake: 3.5 (1-10) units/wk; - TEI: 1950 (508) kcal/d; - Beverage intake at baseline: 23% LNCSB consumers, 98 (47-217) g/d; Excluded from study or analysis: baseline diabetes or unconfirmed status; missing data on diet or covariates; extreme energy intake (top and bottom 1%) | Exposure: Artificially sweetened beverages (diet/sugar-free soft drinks, sports/energy drinks and squashes); - Serving Size: 336 g (12oz); Comparator: continuous intake (per 336 g svg); categorical intake (non-consumers and consumers in tertiles); - Tertiles (range and median intake, g/d); - Tertile 1: 1-59 (36); - Tertile 2: 60-168 (99); - Tertile 3: 169-5848 (290); Assessment methods and timing:; - 7d food diary; - Baseline; Outcome assessment methods and timing:; - Self-report; verified using data internal and external to study through record linkage; - 10.8y | [underlined: T2D by baseline intake], HR (95% CI); Non-consumers: REF; Tertile 1: 0.97 (0.74, 1.27); Tertile 2: 1.16 (0.90, 1.49); Tertile 3: 1.17 (0.93, 1.48); P-trend=0.124; Per svg (336 g): 1.06 (0.93, 1.20); Subgroup analyses:; P-interaction (age)≥0.483; P-interaction (sex)≥0.090; P-interaction (BMI)≥0.424; P-interaction (waist)≥0.182; P-interaction (physical activity)≥0.099; P-interaction (smoking)≥0.274 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, socioeconomic position (occupational social class; educational level), anthropometry, physical activity, family history of diabetes, smoking, alcohol intake; - Other: season (winter/summer), intake of other sweet beverages, fiber intake, saturated fat intake; Limitations:; - Did not account for key confounders: race and/or ethnicity; - Exposure only assessed at baseline; - No preregistered data analysis plan; Funding:; Medical Research Council UK;; Cancer Research UK
Palmer, 2008^28^; PCS, Black Women’s Health Study, U.S.; Analytic N=43,960; Study objective: To examine the association between consumption of sugar-sweetened beverages, weight gain, and incidence of T2D in African American women; Participant characteristics at baseline: African American women; - Age (mean and/or range): ~38 (10)y; 2169y; - Female: 100%; - Race and/or ethnicity: 100% African American; - Socioeconomic position: 15% education ≤12y; - Anthropometry: BMI ~28 (7) kg/m^2^; - Physical activity: 50% with ≥1 hr/wk; - Family history of diabetes: 34%; - Smoking: 16% current; - Alcohol intake: ~1.4 (4) drinks/wk; - TEI: ~1700 (650) kcal/d; - Beverage intake at baseline: NR; Excluded from study or analysis: baseline diabetes; GDM, myocardial infarction, stroke, or cancer; pregnant; <30y at the end of follow-up; missing data; energy intake <500 or >3800 kcal/d | Exposure: Diet soft drinks; - Serving Size: 12oz (336g); Comparator: dichotomous intake (≥1/d vs <1/mo); Assessment methods and timing:; - FFQ; - Baseline (2001); Outcome assessment methods and timing:; - Self-report via biennial questionnaire; - 4y | [underlined: T2D by baseline intake], HR (95% CI); <1 drink/mo: REF; ≥1 drink/d: 1.06 (0.83, 1.36) | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position (years of education), anthropometry, physical activity, family history of diabetes, smoking; - Other: diet (red meat, processed meat, cereal fiber, other beverages), glycemic index, questionnaire cycle; Limitations:; - Did not account for key confounders: alcohol intake; - Analyses based on exposure collected only at baseline; - High attrition rate/missing data with no evidence whether the result was biased due to missing data; - Outcome was self-reported; - No preregistered data analysis plan; Funding:; NCI; NIDDK
Pan, 2012^29^; PCS, NHS-II (Nurses’ Health Study II), U.S.; Analytic N=82,902; Study objective: To evaluate the relation of plain-water intake and the substitution of plain water for SSB and fruit juice with incident T2D in U.S. women; Participant characteristics at baseline: women; - Age (mean and/or range): 36.0 (4.7)y; 2645y; - Female: 100%; - Race and/or ethnicity: Primarily European ancestry; - Socioeconomic position: All nurses; - Anthropometry: BMI ~24 (5) kg/m^2^; - Physical activity: ~19 METs/wk; - Family history of diabetes: 33%; - Smoking: 12% current; - Alcohol intake: ~3 g/d; - TEI: ~1800 kcal/d; - Beverage intake at baseline: NR; Excluded from study or analysis: baseline diabetes; cancer or cardiovascular disease; missing data; implausible total energy intake (<500 or >3500 kcal/d) | Exposure: Artificially sweetened beverages (low-calorie cola with caffeine, low-calorie caffeine-free cola, and other low-calorie beverages); - Serving Size: 1 cup = 240mL; Comparator: continuous intake (svg/d); categorical intake (≤1 cup/wk, 2-4 cups/wk, 5-7 cups/wk, 2-3 cups/d, ≥4 cups/d); Assessment methods and timing:; - FFQ assessing usual intake during previous year.; - 1991, 1995, 1999, 2003 (cumulative average intake); Outcome assessment methods and timing:; - Self-reported via biennial questionnaire; verified with supplementary questionnaire specific to T2D; - Up to 2009 | [underlined: T2D by cumulative average intake], RR (95% CI); ≤1 cup/wk: REF; 2-4 cups/wk: 0.89 (0.77, 1.02); 5-7 cups/wk: 0.92 (0.82, 1.04); 2-3 cups/d: 1.04 (0.93, 1.15); ≥4 cups/d: 1.03 (0.92, 1.16); P-trend=0.04; Per 1 svg/d: 1.03 (1.00, 1.05) | Model adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, anthropometry, physical activity, family history of diabetes, smoking, alcohol intake; - Other: menopausal status and hormone use, oral contraceptive use, AHEI; Limitations:; - Did not account for key confounders: socioeconomic position; - No evidence whether the result was biased due to missing data; - No preregistered data analysis plan; Funding:; NIH
Romaguera, 2013^23^; PCS, EPIC-InterAct, 5 European countries (France, UK, The Netherlands, Germany, and Denmark); Analytic N=26,328 (subcohort = 15,374); Study objective: To evaluate the association of consumption of sweet beverages (juices and nectars, sugar-sweetened soft drinks and artificially sweetened soft drinks) with T2D incidence in European adults.; Participant characteristics at baseline: adults; - Age (mean and/or range): ~52 (9)y; - Female: 62%; - Race and/or ethnicity: NR; - Socioeconomic position: 21% university education; - Anthropometry: BMI ~26 (4) kg/m^2^; - Physical activity: 20% highest activity level (out of 4 levels); - Family history of diabetes: ~19% (NR in Italy, Spain, Germany, and UK); - Smoking: 26% current; - Alcohol intake: ~2 g/d; - TEI: ~2220 (645) kcal/d; - Beverage intake at baseline: 8% ≥1 glass/d of soft drinks, 24% >1-6 glasses/wk; Excluded from study or analysis: baseline diabetes; missing data; lowest and highest 1% for ratio of total energy intake to energy requirement; Italy, Spain, and Umeå (Sweden) where information on type of soft drink consumption was not collected | Exposure: Artificially-sweetened soft drinks; - Serving Size: 336 g (12oz) in continuous analyses; 1 glass svg = 250 g (~8.8oz) in categorical analyses; Comparator: continuous intake (per 336 g svg); categorical intake (<1 glass/mo, 14 glasses/mo, >1-6 glasses/wk, ≥1 glass/d); Assessment methods and timing:; - FFQ or dietary questionnaire (country-specific) assessing usual intake during previous year.; - Baseline; Outcome assessment methods and timing:; - Combination of self-report, linkage to registries, hospital/mortality data; - ~16y | [underlined: T2D by baseline intake], HR (95% CI); <1 glass/mo: REF; 1-4 glasses/mo: 1.05 (0.81, 1.35); >1-6 glasses/wk: 1.18 (1.03, 1.35); ≥1 glass/d: 1.13 (0.85, 1.52); P-trend=0.24; Per svg (336 g): 1.11 (0.95, 1.31); Subgroup analyses:; <55y: 1.37 (1.21, 1.56); ≥55y: 1.63 (1.17, 2.26); P-interaction=0.49; Men: 1.67 (1.27, 2.20); Women: 1.42 (1.16, 1.75); P-interaction=0.94; BMI <25 kg/m^2^: 1.43 (1.14, 1.80); BMI 25-29.9 kg/m^2^: 1.23 (0.99, 1.52); BMI ≥30 kg/m^2^: 1.11 (0.74, 1.65); P-interaction=0.026; Low physical activity: 1.52 (1.23, 1.88); High physical activity: 1.61 (1.19, 2.19); P-interaction=0.73 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, socioeconomic position (educational level), anthropometry, physical activity, family history of diabetes, smoking, alcohol intake; - Other: other sweet beverages; Limitations:; - Did not account for key confounders: race and/or ethnicity; - Exposure only assessed at baseline; - No evidence whether the result was biased due to missing data; - No preregistered data analysis plan; Funding:; EU FP6 Programme
Rose, 2023^30^; NCC, NHS (Nurses’ Health Study), U.S.; Analytic N=2,814; Study objective: To elucidate potential dietary determinants of T2D risk by defining a model that describes habitual beverage consumption profiles in relation to identified networks of circulating plasma biomarkers.; Participant characteristics at baseline: women; - Age (mean and/or range): 56 (7)y; 30-55y; - Female: 100%; - Race and/or ethnicity: Primarily Caucasian; - Socioeconomic position: All nurses; - Anthropometry: BMI 28 (6) kg/m^2^; - Physical activity: ~8 MET hr/wk; - Family history of diabetes: NR; - Smoking: 12% current; 41% former; 48% never; - Alcohol intake: 8% beer; 19% liquor; 9% red wine; 21% white wine; - TEI: ~1800 (450) kcal/d; - Beverage intake at baseline: LNCSB cola: 5.6 (5.5) svg/wk; Caffeine-free LNCS cola: 5.4 (5.0) svg/wk; LNCSB: 3.9 (3.7) svg/wk; Excluded from study or analysis: baseline diabetes; cancer or cardiovascular disease; missing data | Exposure: LNCSB factor (representing higher intake of low-calorie caffeinated and decaffeinated cola and other lowcalorie sweetened beverages relative to other beverage types) identified from EFA; - Serving Size: NR; Comparator: dichotomous intake (low vs high factor score group); Assessment methods and timing:; - FFQ assessing usual intake during previous year.; - 1984, 1986, 1990 (cumulative average intake); Outcome assessment methods and timing:; - Self-reported via biennial questionnaire; verified with supplementary questionnaire specific to T2D | [underlined: T2D by cumulative average intake], OR (95% CI); Low factor score: REF; High factor score: 1.33 (1.03, 1.72); P=0.021 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, anthropometry, physical activity, alcohol factor; - Other: other beverage factors (fruit juice, SSB/LNCSB, caffeine-free), fasting status at blood draw, case-control status, menopausal status, postmenopausal hormone use, aspirin and multivitamin use, modified AHEI score; Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position, family history of diabetes, smoking; - Exposure subject to measurement error; - No evidence whether the result was biased due to missing data; - No preregistered data analysis plan; Funding:; NIH
Sakurai, 2014^31^; PCS, Japan; Analytic N=2,037; Study objective: To investigate the association between SSB and diet soda consumption and the incidence of T2D in Japanese men.; Participant characteristics at baseline: lean middle-aged Japanese men; - Age (mean and/or range): 46.2y; 35-55y; - Female: 0%; - Race and/or ethnicity: All Japanese; - Socioeconomic position: All employed at factory; - Anthropometry: BMI 23.4 kg/m^2^; - Physical activity: 28% habitual exercise; - Family history of diabetes: 13%; - Smoking: 53% current; 15% former; 32% never; - Alcohol intake: 15% never, 11% occasional, 32% <20g/d, 42% ≥20g/d; - TEI: 1998-2627 kcal/d; - Beverage intake at baseline: 1% consumed LNCSB ≥1 svg/d; median daily intake (range): 0.0 (0.0-4.7) svg; Excluded from study or analysis: baseline diabetes or FPG ≥126 mg/dL or HbA1c ≥6.5%; energy intake <500 or >5000 kcal/d; missing data on SSB; loss to follow-up | Exposure: “Non-calorie carbonated soft drinks”; - Serving Size: 237mL or 8oz; Comparator: categorical intake; - Rare/never (n=1620); - More often than rare/never but <1 svg/wk (n=198); - ≥1 svg/wk (n=219); Assessment methods and timing:; - Validated diet history questionnaire on intake during previous month; - Baseline; Outcome assessment methods and timing:; - Biomarkers (FPG ≥126 mg/dL and/or HbA1c ≥6.5%); - 5.5 (1.8)y (annually) | [underlined: T2D by baseline intake], HR (95% CI); Rare/never: REF; >Rare/never but <1 svg/wk: 1.14 (0.66, 1.95); ≥1 svg/wk: 1.71 (1.11, 2.63); P-trend=0.015 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity (Japanese), anthropometry, physical activity, family history of diabetes, smoking, alcohol intake; - Other: hypertension dyslipidemia, diet treatment for chronic disease, total fiber intake, other beverage consumption (SSB, fruit juice, vegetable juice, coffee); Limitations:; - Did not account for key confounders: socioeconomic position; - Exposure only assessed at baseline; - No evidence whether the result was biased due to missing data; - No preregistered data analysis plan; Funding:; Ministry of Health, Labor, and Welfare, Health and Labor Sciences; Ministry of Education, Culture, Sports, Science and Technology of Japan for Scientific Research; Japan Arteriosclerosis Prevention Fund
Schulze, 2004^32^; PCS, NHS-II (Nurses’ Health Study II), U.S.; Analytic N=91,249; Study objective: To examine the association between consumption of sugar-sweetened beverages and weight change and risk of T2D in women.; Participant characteristics at baseline: women; - Age (mean and/or range): ~36 (4.7)y; 2444y; - Female: 100%; - Race and/or ethnicity: Primarily European ancestry; - Socioeconomic position: All nurses; - Anthropometry: BMI ~24.4 kg/m^2^; - Physical activity: ~19 METs/wk; - Family history of diabetes: ~16% in a firstdegree relative; - Smoking: 12% current; - Alcohol intake: ~3 g/d; - TEI: ~1800 kcal/d; - Beverage intake at baseline: NR; Excluded from study or analysis: baseline diabetes; cancer or cardiovascular disease; missing data; implausible total energy intake (<500 or >3500 kcal/d) | Exposure: “Low-calorie cola with caffeine”, “low-calorie caffeine-free cola”, and “other low-calorie beverages”; - Serving Size: NR; Comparator: categorical intake (<1/mo, 1-4/mo, 2-6/wk, ≥1/d); Assessment methods and timing:; - FFQ assessing usual intake during previous year.; - 1991, 1995; Outcome assessment methods and timing:; - Self-reported via biennial questionnaire; verified with supplementary questionnaire specific to T2D; - 8y | [underlined: T2D by average intake], RR (95% CI); <1/mo (REF); ≥1/d: 1.21 (0.97, 1.50); P-trend=0.12 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, anthropometry, physical activity, family history of diabetes, smoking, alcohol intake; - Other: postmenopausal hormone use, oral contraceptive use, intake of cereal fiber, magnesium, trans-fat, ratio of polyunsaturated to saturated fat, and other sugarsweetened beverage consumption (other than the main exposure, depending on model); Results were similar when adjusting for caffeine, red meat, french fries, processed meat, sweets, snacks, vegetables, and fruit; Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position; - No evidence whether the result was biased due to missing data; - No preregistered data analysis plan; Funding:; NIH; European Association for the Study of Diabetes/American Diabetes Association; German Academic Exchange Service (DAAD)
von Ruesten, 2013^33^; PCS, EPIC-Potsdam, Germany Analytic N=23,531; Study objective: To give a comprehensive overview on health-related foods in relation to major chronic diseases based on 8 years of follow-up; Participant characteristics at baseline: adults; - Age (mean and/or range): 35-65y; - Female: 61%; - Race and/or ethnicity: NR; - Socioeconomic position: NR; - Anthropometry: NR; - Physical activity: NR; - Family history of diabetes: NR; - Smoking: NR; - Alcohol intake: NR; - TEI: NR; - Beverage intake at baseline: median 0 g/d of low-energy soft drinks; Excluded from study or analysis: baseline diabetes; CVD or cancer; missing data; energy intake >800 or >6000 kcal/d | Exposure: Low-energy soft drinks (calorie-reduced cola, calorie-reduced lemonade); - Serving Size: 200g; Comparator: continuous intake (per 1 svg/d); Assessment methods and timing:; - FFQ assessing usual intake during previous year.; - Baseline; Outcome assessment methods and timing:; - Self-report or registries; medically verified with physician inquiry; - 8y | [underlined: T2D by baseline intake], HR (95% CI); Fully-adjusted model: 0.92 (0.78, 1.08); Further adjusted for other food groups: 0.95 (0.82, 1.09) | Model adjustments:; - TEI: yes; - Key confounders: sex, age, socioeconomic position (education), anthropometry, physical activity, smoking, alcohol intake; - Other: prevalent hypertension at baseline, history of high blood lipid levels at baseline, vitamin supplementation, non-consumption of the respective food group, 45 food groups; Limitations:; - Did not account for key confounders: race and/or ethnicity, family history of diabetes; - Exposure only assessed at baseline; - No evidence whether the result was biased due to missing data; - No preregistered data analysis plan; Funding:; Federal Ministry of Science (Germany); European Community; German Cancer Aid

a Abbreviations: ASB: artificial sweetened beverage(s); BMI: body mass index; CI: confidence interval; CVD: cardiovascular disease; d: day(s); dL: deciliter(S); EFA: exploratory factor analysis; EPIC: European Prospective Investigations into Cancer and Nutrition Study; FFQ: food frequency questionnaire; g: gram(s); HbA1C: hemoglobin A1C; hr: hour; HR: hazard ratio; IAUC: incremental area under the curve; kcal: kilocalorie(s); kg: kilogram(s); LNCSB: low- and no-calorie sweetened beverage(s); m: meter(s); mg: milligram(s); min: minute(s); mL: milliliter(s); N/A: not applicable; NCC: nested case control study; NIDDK: National Institute of Diabetes and Digestive and Kidney Diseases; NIH: National Institutes of Health; nmol: nanomole(s); NR: not reported; NS: not significant; OGTT: oral glucose tolerance test; OR: odds ratio; PCS: prospective cohort study; REF: reference group; SD: standard deviation; SE: standard error; SSB: sugar-sweetened beverage(s); svg: serving(s); T2D: type 2 diabetes; TEI: total energy intake; μmol: micromole(s); wk: week(s); y: year(s)

Table 11 Risk of bias for randomized controlled trials examining low- and no-calorie sweetened beverage consumption in adults and older adults and risk of type 2 diabetes^a^

Article | Randomization | Deviations from intended interventions (per protocol) | Missing outcome data | Outcome measurement | Selection of reported result | Overall risk of bias
Ebbeling, 2020^2^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Engel, 2018^3^ | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Harrold, 2023^4^ | LOW | LOW | SOME CONCERNS | LOW | LOW | SOME CONCERNS
Harrold, 2024^5^ | LOW | LOW | SOME CONCERNS | LOW | LOW | SOME CONCERNS
Kendig, 2023^6^ | SOME CONCERNS | HIGH | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Madjd, 2015^7^ | LOW | SOME CONCERNS | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Madjd, 2018^8^ | LOW | SOME CONCERNS* | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Peters, 2014^10^ | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Peters, 2016^9^ | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Tate, 2012^11^ | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Viveros-Watty, 2022^12^ | LOW | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS

a Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898.31462531

Table 12 Risk of bias for observational studies examining low- and no-calorie sweetened beverage consumption in adults and older adults and risk of type 2 diabetes^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of reported result | Overall risk of bias
Bazzano, 2008^13^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Bhupathiraju, 2013^14^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Chen, 2023^15^ | LOW* | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
de Koning, 2011^16^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Drouin-Chartier, 2019^17^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Fagherazzi, 2013^18^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Gardener, 2018^19^ | HIGH | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Hirahatake, 2019^20^ | LOW* | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Huang, 2017^21^ | LOW* | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Imamura, 2019^22^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Jensen, 2020^24^ | HIGH | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
McNaughton, 2008^25^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Nettleton, 2009^26^ | HIGH | HIGH | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
O’Connor, 2016^27^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Palmer, 2008^28^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Pan, 2012^29^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Romaguera, 2013^23^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Rose, 2023^30^ | HIGH | HIGH | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Sakurai, 2014^31^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Schulze, 2004^32^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
von Ruesten, 2013^33^ | HIGH | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH

a Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the “Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)” tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602 .) *Low risk of bias except for concerns about uncontrolled confounding.