# Results

## Literature search and screening results

The literature search was conducted to identify all potentially relevant articles for 2 systematic reviews assessing beverages and risk of type 2 diabetes: sugar-sweetened beverages^†^ and low- and no-calorie sweetened beverages. The literature search (Appendix 2) yielded 16,910 search results after the removal of duplicates (see Figure 2). Dual-screening resulted in the exclusion of 14,523 titles, 2,054 abstracts, and 281 full-text articles. Reasons for full-text exclusion are in Appendix 3. Five additional articles were identified from the manual search. The body of evidence included 33 articles on low- and no-calorie sweetened beverages:

- Infants, children, and adolescents: 1 article^1^
- Adults and older adults: 32 articles^2–33^

† Giovannucci E, Taylor CA, Deierlein AL, . Sugar-Sweetened Beverages and Risk of Type 2 Diabetes: A Systematic Review. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review; 2025. 10.52570/NESR.DGAC2025.SR14

Figure 2 Literature search and screen flowchart

The literature search in PubMed, Embase, Cochrane, and CINAHL, retrieved 16,910 records after removing duplicates. Five were found through other manual search methods. 14,523 titles, 2054 abstracts, and 281 full-texts were excluded. 57 articles were included across the two systematic reviews examining beverage consumption and risk of type 2 diabetes. 33 articles were included in the systematic review on low- and no-calorie sweetened beverages.

## Infants, children, and adolescents

### Description of the evidence

One article examined the relationship between LNCSB consumption in infants, children, and adolescents and risk of type 2 diabetes. The article was a prospective cohort study (Study of Latino Adolescents at Risk for Diabetes, SOLAR), conducted in the U.S. in a sample of 98 Hispanic adolescents (14.0±1.8 years old, 43% female) with overweight and obesity (Table 7).^1^ The study did not report data on socioeconomic position. Adolescents were divided into 3 groups based on their intake (measured using two 24-hour dietary recalls) of artificially-sweetened beverages (ASB) at baseline and 1-year follow-up:

- Control (n=75): no ASB intake at baseline or 1-year follow-up
- ASB initiators (n=14): no ASB at baseline, but ASB at 1-year follow-up
- Chronic ASB consumers (n=9): ASB at baseline (1.4±0.8 servings per day) and 1-year follow-up

Fasting blood samples, oral glucose tolerance, and frequently sampled intravenous glucose tolerance tests were collected using standard methods at baseline and 1-year follow-up, and the following outcomes were reported: fasting blood glucose, fasting blood insulin, 2-hour oral glucose tolerance test (OGTT), glucose incremental area under the curve (IAUC), insulin IAUC, and hemoglobin A1C (HbA1C). The study also reported computer-calculated measures of insulin sensitivity, acute insulin response, and disposition index of beta cell function.

### Synthesis of the evidence

Davis et al^1^ found that adolescents who were chronic consumers of ASB had significant increases in HbA1C over 1-year follow-up, while adolescents who were ASB initiators or did not drink ASB (control) maintained HbA1C levels. Fasting blood glucose and insulin IAUC were reduced over 1-year follow-up, but there was no significant difference between adolescents in the control and ASB groups. There was also no significant difference between groups for fasting insulin, 2-hour OGTT, glucose IAUC, insulin sensitivity, acute insulin response, or disposition index of beta cell function. The study adjusted for total energy intake but did not account for several key confounders (Table 8). While the literature search was comprehensive, a search of the gray literature was not done, which may increase the possibility of publication bias. However, publication bias was determined to be of less concern since the single study reported nonsignificant findings.

### Conclusion statement and grade

The Committee was not able to develop a conclusion statement to answer the question “What is the relationship between low- and no-calorie sweetened beverage consumption and risk of type 2 diabetes?” based on their review of evidence in infants, children, and adolescents (Table 5).

Table 5 Conclusion statement and grade for low- and no-calorie sweetened beverage consumption in infants, children, and adolescents and risk of type 2 diabetes

Conclusion | A conclusion statement cannot be drawn about the relationship between low- and no-calorie sweetened Statement beverage consumption by infants, children, and adolescents and risk of type 2 diabetes because there is not enough evidence available.
Grade | Grade Not Assignable
Body of Evidence | 1 article (prospective cohort study in adolescents)
Rationale | There was 1 eligible article examining low- and no-calorie sweetened beverage consumption and risk of type 2 diabetes in adolescents and no articles examining this relationship in infants or children.

## Adults and older adults

### Description of the evidence

Thirty-two articles (23 studies) examined the relationship between LNCSB consumption in adults and older adults and risk of type 2 diabetes. Eleven articles^2–12^ were from 8 randomized controlled trials (RCT) and 21 articles were from 15 observational studies (1 nested case control^30^ and 14 prospective cohort studies^13–29,31–33^). Evidence for LNCSB consumption in adults and older adults and risk of type 2 diabetes is summarized in Table 9 (RCT) and Table 10 (observational). Risk of bias assessments for each article are detailed in Table 11 (RCT) and Table 12 (observational).

#### Population

Among trials, mean baseline age ranged from 21 to 47 years. One trial^7,8^ enrolled females only, 5 trials^3–5,9–12^ had >60% female enrollment, 1 trial^2^ had 60% male enrollment, and 1 trial^6^ enrolled men and women but did not report the percentage of each. Analytic sample size of study groups among the trials ranged from N=45 to N=313.

Among observational studies, mean baseline age ranged from 25 to 69 years. Three studies were conducted in participants with a mean age ≥60 years.^19,21,26^ Five studies (7 articles^13,18,21,28–30,32^) enrolled only females and 2 studies^16,31^ enrolled only males. Sample sizes ranged from N=1,142 to N=198,636. Seven articles had analytic sample sizes less than 10,000 participants.^19,20,24–26,30,31^

Multiple articles were from the same trial or cohort study (such as EPIC, the European Prospective Investigation into Cancer and Nutrition) and were included when the article reported unique data. Studies were conducted in populations from the following countries:

- Australia: 1 article from an RCT^6^
- Denmark: 1 article from an RCT^3^
- France: 1 article from the EPIC-E3N (Etude Epidémiologique auprès de femmes de la Mutuelle Générale de l’Education Nationale) cohort^18^
- Germany: 1 article from the EPIC-Potsdam study^33^
- Iran: 2 articles from the same RCT^7,8^
- Japan: 1 article from an unnamed cohort study^31^
- Mexico: 1 article from an RCT^12^
- United Kingdom: 4 articles (2 articles from the SWITCH trial^4,5^, 1 article from the EPIC-Norfolk cohort^27^, and 1 article from the Whitehall-II cohort^25^)
- United States: 18 articles (4 articles from 3 trials^2,9–11^ and 14 articles from 9 cohorts^13–17,19–21,24,26,28–30,32^)
  ○ The cohorts included: Black Women’s Health Study^28^; Coronary Artery Risk Development in Young Adults Study (CARDIA)^20^; Health Professionals Follow-Up Study (HPFS)^14–17^; Multi-Ethnic Study of Atherosclerosis (MESA)^26^; Northern Manhattan Study^19^; Nurses’ Health Study (NHS)^13–15,17,30^; Nurses’ Health Study II (NHS-II)^15,17,29,32^; Strong Heart Family Study^24^; Women’s Health Initiative^21^
- Multiple European countries: 2 articles from the EPIC-InterAct study^22,23^

##### Race and/or ethnicity

Among trials, 5 trials (7 articles^3–8,12^) did not report data on race and/or ethnicity. Three trials from the U.S. were diverse in terms of participant race and/or ethnicity.^2,9–11^ Among observational studies, 6 studies (11 articles^13–17,21,25,27,29,30,32^) were in predominantly white/Caucasian populations (>85%). Five studies from the United States enrolled majority racial and/or ethnic minorities: 100% American Indian^24^; 100% African American^28^; 50% Black and 50% White^20^; 53% Hispanic, 22% Black, 23% White, 2% Other^19^; 43% White, 23% African American, 21% Hispanic, 12% Chinese^26^. Four articles (all from the EPIC study) did not report data on race and/or ethnicity.^18,22,23,33^

##### Socioeconomic position

Among trials, 2 reported >50% of participants with a college degree or higher.^2,11^ Six trials (9 articles) did not report data on socioeconomic position.^3–10,12^ Among observational studies, 4 studies (9 articles^13–18,29,30,32^) enrolled primarily well-educated samples; 9 studies (10 articles^20–28,31^) were diverse in terms of participant education and/or income levels and 2 studies^19,33^ did not report data on socioeconomic position.

##### Health status

Among trials, 6 trials (9 articles^3–5,7–12^) included participants with overweight or obesity and had inclusion criteria for BMI ≥25 kg/m^2^ or ≥30 kg/m^2^. Two trials included participants across BMI weight status categories and both had inclusion criteria related to habitual sugar-sweetened beverage consumption at baseline.^2,6^ Three trials^3–5,7,8^ excluded current smokers and 4 trials^2,6,9,10,12^ did not report data on smoking; in the trial conducted by Tate et al^11^, 8% of participants were current smokers and 25% were former smokers. No trials reported data on family history of diabetes.

Among observational studies, participant mean BMI at baseline ranged from 23 to 28 kg/m^2^. Most articles (14 out of 21) reported a mean BMI ≥25 kg/m^2^. One study did not report baseline anthropometry.^33^ Most articles (16 out of 21) reported current smoking in 9% to 30% of participants; 2 articles^24,31^ had >30% of current smokers, 1 article^21^ reported current smoking in 4% of female participants, and 2 articles^18,33^ did not report data on smoking. The percentage of participants with family history of diabetes ranged from 10% to 34%; 5 articles^19,24–26,33^ did not report data on family history of diabetes.

##### Intervention/exposure and comparator

The intervention or exposure for this systematic review question was LNCSB. Eligible comparators were consumption of different amounts of LNCSB (including no consumption and versions diluted with water) or water. Studies that compared LNCSB to sugar-sweetened beverages were included in the systematic review on sugar-sweetened beverages.^*^

* Giovannucci E, Taylor CA, Deierlein AL, . Sugar-Sweetened Beverages and Risk of Type 2 Diabetes: A Systematic Review. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review; 2025. 10.52570/NESR.DGAC2025.SR14

Among trials, all but 2 studies compared LNCSB consumption to water. Viveros-Watty et al^12^ compared different amounts of artificially-sweetened beverage consumption and Tate et al^11^ compared diet beverage consumption to an “attention control” group with equal treatment contact time and attention. The interventions and comparators in the trials are detailed below:

- Ebbeling et al^2^: a 52-week intervention in which the intervention group was instructed to drink artificially-sweetened beverages at the same number of servings per day as their usual consumption of sugar-sweetened beverages compared to a group that was instructed to drink water (but not artificially- or sugar-sweetened beverages); both groups had beverages delivered to their home.
- Engel et al^3^: a 26-week intervention in which the intervention group drank aspartame-sweetened diet cola compared to a group that drank still mineral water; both groups consumed 1 liter per day of the beverage.
- Harrold et al^4,5^: a 12-week weight loss intervention^4^ (and 40-week weight maintenance phase^5^) in which the intervention group consumed non-nutritive sweetened beverages compared to a group who drank still or carbonated water; both groups drank ≥2 servings per day of the beverage
- Kendig et al^6^: a 12-week intervention in which the intervention group drank commercially-available diet drinks sweetened with aspartame, acesulfame-K, and sucralose compared to the control group who drank water; both groups had beverages delivered to their home and consumed 4.5 liters per week as twelve 375-mL cans.
- Madjd et al^7,8^: a 24-week weight loss intervention^7^ (and 52-week weight maintenance phase^8^) in which the intervention group drank a 250 mL serving of diet beverages once a day after lunch (5 days a week, with water the remainder of the week) compared to a group who replaced habitual intake of diet beverages with a 250 mL glass of water after lunch; both groups also consumed a hypo-energetic diet
- Peters et al^9,10^: a 12-week weight loss intervention^10^ (and 40-week weight maintenance phase^9^) in which the intervention group consumed non-nutritive sweetened beverages compared to a group that consumed water and refrained from non-nutritive sweetened beverages; both groups drank ≥24 fluid ounces per day (710 ml) of the beverage and also participated in a behavioral weight loss treatment program that included physical activity and individualized energy targets to achieve a 1-2 pound weight loss per week.
- Tate et al^11^: a 26-week weight loss intervention in which the intervention group was encouraged to replace ≥2 servings a day (≥200 kcal) of caloric beverages with diet beverages (provided in four 355-500 mL single-servings each day). This was in comparison to an “attention control” group that participated in monthly group sessions, weigh-ins, and weekly monitoring, and received general weight-loss information; participants in the “attention control” group were not encouraged to change beverage intake and were not provided with beverages.
- Viveros-Watty et al^12^: a 12-week intervention among habitual consumers of artificially-sweetened beverages (at least three 250-mL servings per week) in which the intervention group was asked not to consume artificially-sweetened beverages (but were allowed other beverages with no artificial sweeteners) compared to the control group that consumed their usual intake artificially-sweetened beverages; both groups continued their normal food habits.

Among observational studies, 12 articles^13–16,19–23,27,29,33^ examined continuous beverage intake (e.g., servings per day); whereas, 9 articles^17,18,24–26,28,30–32^ only compared intake across categories (e.g., tertiles, quintiles). Fourteen articles examined LNCSB intake using a food frequency questionnaire^13–17,19,24–26,28–30,32,33^; 4 articles^18,20,21,31^ used a diet history questionnaire and 1 article^27^ used a 7-day food diary. Two articles from the EPIC-InterAct study used either a dietary questionnaire or country-specific food frequency questionnaire to assess usual intake during the previous year.^22,23^ Twelve articles^18,19,21–28,31,33^ examined beverage intake at baseline only; 9 articles^13–17,20,29,30,32^ (4 studies) examined change in beverage intake over time.

#### Outcome

The following outcomes were reported:

- Fasting blood glucose: 11 articles^2–5,7–12^ from 7 trials
- Fasting insulin: 7 articles^2–5,7,8,12^ from 5 trials
- Glucose tolerance/insulin resistance: 6 articles^2,3,6–8,12^ from 5 trials
- Hemoglobin A1C: 4 articles^4,5,7,8^ from 2 trials
- Type 2 diabetes: 21 articles^13–33^ from 15 observational studies

All trials collected fasted blood samples and/or measured oral glucose tolerance using standard methods at baseline and follow-up. Four articles had a follow-up duration of 52 weeks or longer^2,5,8,9^; 3 articles^3,7,11^ had a follow-up duration of 6 months and 4 articles^4,6,10,12^ had a follow-up duration of 12 weeks. No included trials examined incidence of impaired fasting blood glucose, prediabetes, or incidence of type 2 diabetes.

Among observational studies, 14 out of 21 articles used self-report of type 2 diabetes diagnosis, but all verified the accuracy of diagnosis.^13–19,21,24,27–30,32^ Four articles collected fasting blood samples to confirm diagnosis.^20,25,26,31^ Three articles used a combination of self-report, linkage to registries, and hospital/mortality data.^22,23,33^ Most studies reported type 2 diabetes incidence using standard criteria or definitions (such as criteria from the National Diabetes Data Group, American Diabetes Association, or World Health Organization for biomarkers) and/or treatment with hypoglycemic medication (insulin or oral hypoglycemic agent). Average follow-up duration ranged from 5.5 to 25 years.

### Synthesis of the evidence

There was evidence from interventions that LNCSB consumption, when compared to water, had no effect on fasting blood glucose, fasting insulin, glucose tolerance/insulin resistance, and hemoglobin A1C. There was some evidence from observational studies that higher LNCSB consumption was not associated with higher risk of type 2 diabetes. The results for each reported outcome are detailed below:

#### Fasting blood glucose

Out of 7 trials, 6 reported a null effect of LNCSB consumption on change in fasting blood glucose^2–5,7–11^; only Engel et al^3^ adjusted for total energy intake. Viveros-Watty et al^12^ found that those who consumed their usual intake of artificially-sweetened beverages had increased percentage of change in fasting plasma glucose compared to those who did not drink artificially-sweetened beverages; there was no difference in energy intake between groups during the intervention.

#### Fasting insulin

Out of 5 trials, 3 reported a null effect of LNCSB consumption on change in fasting insulin^2–5^; of these, only Engel et al^3^ adjusted for total energy intake. Two trials reported an effect of LNCSB consumption on fasting blood insulin^7,8,12^; in both trials, there was no statistically significant difference between groups for total energy intake at baseline. Viveros-Watty et al^12^ found that those who consumed their usual intake of artificiallysweetened beverages had increased percentage of change in fasting insulin compared to those who did not drink artificially-sweetened beverages; there was no difference in energy intake between groups during the intervention. Madjd et al^7,8^ found that participants who were randomized to water had greater improvement in fasting insulin compared to those who drank diet beverages, and this was significant after the 24-week weight loss intervention^7^ and at 12- and 18-month follow-up^8^.

#### Glucose tolerance/insulin resistance

Out of 5 trials, 3 reported a null effect of LNCSB consumption on glucose tolerance/insulin resistance^2,3,6^; only 1 trial^3^ adjusted for total energy intake. Engel et al^3^ found similar changes in measures of insulin sensitivity assessed by a 120-minute oral glucose tolerance test between participants who drank aspartame-sweetened cola compared to those that drank water. Ebbeling et al^2^ found no difference in insulin sensitivity between participants who drank artificially sweetened beverages compared to those who drank water. Kendig et al^6^ found similar changes in a 60-minute oral glucose tolerance test over 12 weeks between participants that drank artificially sweetened beverages compared to those that drank water.

Two trials reported an effect of LNCSB consumption on glucose tolerance/insulin resistance^7,8,12^; in both trials, there was no statistically significant difference between groups for total energy intake at baseline. Viveros-Watty et al^12^ found that those who consumed their usual intake of artificially-sweetened beverages had increased percentage of change in homeostatic model assessment for insulin resistance (HOMA-IR) compared to those who did not drink artificially-sweetened beverages; there was no difference in energy intake between groups during the intervention. Madjd et al^7,8^ found that women who drank water had greater improvement in 2-hour post-prandial glucose and HOMA-IR compared to women who drank diet beverages, and this was significant after the 24-week weight loss intervention^7^ and at 12- and 18-month follow-up^8^.

#### Hemoglobin A1C

Two trials reported a mix of null and significant results for the relationship between LNCSB consumption and HbA1C. Madjd et al^7,8^ found no difference between groups in HbA1C after a 24-week weight loss intervention^7^ or 12-month follow-up, but women who drank water had greater improvements in HbA1C compared to those who drank diet beverages at 18-month follow-up (after the 52-week weight maintenance phase^8^). Harrold et al^4,5^ found that water consumption resulted in greater improvements in HbA1C compared to diet beverage consumption after 12 weeks,^4^ but this was no longer significant at 52 weeks.^5^

#### Type 2 diabetes

Studies evaluating the association between LNCSB intake and incidence of type 2 diabetes reported different effect measures (hazard ratio, risk ratio, and odds ratio). Some effect measures indicated no change in risk of type 2 diabetes at 5 to 25 years of follow-up. Out of 21 articles, 10 articles (9 studies) reported no association between LNCSB consumption and incidence of type 2 diabetes.^16,20,22–25,27,28,32,33^ All studies accounted for anthropometry at baseline, and all but 1 study^25^ controlled for total energy intake. Most articles used a food frequency questionnaire to assess LNCSB consumption; 1 article^20^ used a diet history questionnaire and 1 article^27^ used a 7-day food diary. Most articles examined LNCSB at baseline only; 3 articles^16,20,32^ examined change in LNCSB intake over time.

Eleven articles (8 studies) reported an association between higher amounts of LNCSB consumed and higher risk of type 2 diabetes.^13–15,17–19,21,26,29–31^ All studies accounted for anthropometry at baseline, and all but 1 study^29^ controlled for total energy intake. Most articles used a food frequency questionnaire to assess LNCSB consumption; 3 articles^18,21,31^ used a diet history questionnaire. Five articles^18,19,21,26,31^ examined LNCSB at baseline only; 6 articles^13–15,17,29,30^ examined change in LNCSB intake over time.

### Conclusion statement and grade

The Committee developed a conclusion statement to answer the question “What is the relationship between low- and no-calorie sweetened beverage consumption and risk of type 2 diabetes?” based on their review of evidence in adults and older adults (Table 6).

Table 6 Conclusion statement and grade for low- and no-calorie sweetened beverage consumption in adults and older adults and risk of type 2 diabetes

Conclusion Statement | Low- and no-calorie sweetened beverage consumption by adults and older adults may not be associated with risk of type 2 diabetes. This conclusion statement is based on evidence graded as limited.
Grade | Limited
Body of Evidence | 32 articles: 11 from RCT, 1 nested case control, 20 from prospective cohort studies
Consistency | Several concerns due to considerable variation in the direction and magnitude of effects
Precision | Few concerns due to large sample sizes and adequate number of cases
Risk of bias | Several concerns due to potential for confounding and missing data
Directness | Few concerns with directness across studies
Generalizability | Some concerns due to low diversity in reported race and/or ethnicity and socioeconomic position

#### Assessment of the evidence

The body of evidence underlying the conclusion statement includes 11 articles from randomized controlled trials and 21 articles from observational studies. The strength of the evidence was graded based on an assessment of 5 grading elements, as described below. While the literature search was comprehensive, a search of the gray literature was not done, which may increase the possibility of publication bias. However, publication bias was determined to be of less concern given that the body of evidence includes multiple small and large studies that reported a mix of significant and nonsignificant findings.

##### Consistency

The direction of findings was generally inconsistent. All trials compared LNCSB consumption with water, and most found null effects. All observational studies examined the relationship between different levels of LNCSB consumption and incidence of type 2 diabetes, and there was a mix of null and positive associations. Studies that supported the association between higher LNCSB consumption and higher incidence of type 2 diabetes may be related to reverse causality, as individuals may consume more LNCSB as a means to reduce caloric intake and/or lose or maintain weight.

##### Precision

Some trials had concerns with sufficient power (i.e., the study did not report a power calculation or was based on reported power calculations that were not sufficiently powered). Most observational studies had large sample sizes and some demonstrated statistically significant effects with minimal variance (e.g., narrow confidence intervals). There were some concerns due to varying definitions of the exposures and the metrics used to measure them.

##### Risk of bias

Most trials did not include a data analysis plan in the trial registry. There were concerns with risk of bias due to confounding as only 3 out of 21 articles of observational studies accounted for all key confounders. Several observational studies did not account for race and/or ethnicity, socioeconomic position, and/or family history of diabetes. Some articles were at higher risk of exposure mismeasurement for not accounting for change in beverage intake that may occur during follow-up. There were also concerns due to missing data (large study cohorts with high attrition or exclusion) and selection of the reported results, as none of the observational studies had a pre-determined analysis plan.

##### Directness

Most studies were designed to directly examine the relationship between LNCSB consumption and risk of type 2 diabetes. Two trials^3,12^ examined insulin sensitivity as the primary outcome, whereas the main objective of other trials was to examine change in weight. Most observational studies were designed to directly answer the research question.

##### Generalizability

The review included studies from 12 countries with similar HDI classification as the United States. The body of evidence has applicable interventions/exposures and outcomes relative to the U.S. population, but there were concerns with low diversity in reported race and/or ethnicity and socioeconomic position. Over half (12 out 23) of the studies were conducted in the United States, and of these 9 were diverse in racial and ethnic representation and socioeconomic position. The body of evidence included many participants with overweight or obesity, or other risk factors for cardiometabolic disease.