# Plain language summary

### What is the question?

The question is: What is the relationship between low- and no-calorie sweetened beverage consumption and risk of type 2 diabetes? The populations of interest for this question include infants, children, adolescents, adults, and older adults.

### Why was this question asked?

This systematic review was conducted by the 2025 Dietary Guidelines Advisory Committee as part of the process to develop the Dietary Guidelines for Americans, 2025-2030.

### How was this question answered?

The Committee conducted a systematic review to answer this question with support from the USDA Nutrition Evidence Systematic Review team.

### What is the answer to the question?

#### Infants, children, and adolescents

- A conclusion statement cannot be drawn about the relationship between low- and no-calorie sweetened beverage consumption by infants, children, and adolescents and risk of type 2 diabetes because there is not enough evidence available.

#### Adults and older adults

- Low- and no-calorie sweetened beverage consumption by adults and older adults may not be associated with risk of type 2 diabetes. This conclusion statement is based on evidence graded as limited.

### How up-to-date is this systematic review?

Conclusion statements from this review are based on articles published between January 2000 and January 2024.