# Appendix 2 Literature search strategy

This search was first run on July 5, 2022, and then periodically run using NESR’s continuous evidence monitoring methods until January 9, 2024.^*^

* USDA Nutrition Evidence Systematic Review Branch. Chapter 10: Continuous Evidence Monitoring. In: USDA Nutrition Evidence Systematic Review: Methodology Manual. February 2023. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://nesr.usda.gov/methodology-overview.

[underlined: Database: PubMed]

Provider: U.S. National Library of Medicine

Date(s) Searched: July 5, 2022 (initial search); July 5, 2022 – January 9, 2024 (continuous evidence monitoring)

Dates Covered: January 1, 2000 – January 9, 2024

Table A 2 Search for PubMed

Search # | Concept | String
#1 | Beverages | “Beverages”[Mesh:NoExp] OR “Sugar Sweetened Beverages”[MeSH] OR “Artificially Sweetened Beverages”[Mesh] OR diet drink*[tiab] OR sweetening agent*[tiab] OR artificially sweet*[tiab] OR beverage[tiab] OR beverages[tiab] OR sports drink*[tiab] OR fortified drink*[tiab] OR sweetened drink*[tiab] OR sweet drink*[tiab] OR sugary drink*[tiab] OR dairy drink*[tiab] OR chocolate drink*[tiab] OR smoothie*[tiab] OR carbonated drink*[tiab] OR soft drink*[tiab] OR soda[tiab] OR sodas[tiab] OR caffeinated drink*[tiab] OR “Drinking Water”[Mesh] OR drinking water[tiab] OR bottled water[tiab] OR “Carbonated Beverages”[Mesh] OR carbonated water[tiab] OR sparkling water[tiab] OR flavored water[tiab] OR flavoured water[tiab] OR flavoured drink[tiab] OR flavored drink*[tiab] OR “Energy Drinks”[Mesh] OR energy drink*[tiab] OR “Fruit and Vegetable Juices”[Mesh] OR juice[tiab] OR juices[tiab] OR fruit drink*[tiab] OR fizzy drink*[tiab] OR “Coffee”[Mesh] OR coffee[tiab] OR “Tea”[Mesh] OR tea[tiab] OR “Milk”[Mesh:NoExp] OR milk[tiab] OR “Soy Milk”[Mesh] OR soymilk[tiab] OR “Buttermilk”[Mesh] OR buttermilk[tiab] OR liquid[tiab] OR liquids[tiab]
#2 | Type two diabetes | “Diabetes Mellitus”[Mesh:NoExp] OR “Diabetes Mellitus, Type 2”[Mesh] OR “type 2 diabet*”[tiab] OR “T2D”[tiab] OR “adult onset diabetes”[tiab] OR “Prediabetic State”[Mesh] OR “prediabet*”[tiab] OR “pre diabet*”[tiab] OR “Insulin Resistance”[Mesh] OR “insulin resistance”[tiab] OR “insulin resistant”[tiab] OR “glucose intolerance”[tiab] OR “glucose intolerant”[tiab] OR “glucose tolerance”[tiab] OR “glucose tolerant”[tiab] OR “Glycated Hemoglobin A”[Mesh] OR “hemoglobin A1c”[tiab] OR hba1c[tiab] OR “hba 1c”[tiab] OR “haemoglobin A1c”[tiab] OR “Hyperglycemia”[Mesh] OR “hyperglycemia”[tiab] OR hyperglycaemia[tiab] OR “Hypoglycemia”[Mesh] OR “hypoglycemia”[tiab] OR hypoglycaemia[tiab] OR ((impaired[tiab] OR glucose[tiab]) AND fasting[tiab]) OR “blood glucose”[MeSH] OR “blood glucose”[tiab] OR “plasma glucose”[tiab] OR “serum glucose”[tiab] OR “glycemi*”[tiab] OR glycaemi*[tiab] OR “blood sugar”[tiab] OR dysglycemi*[tiab] OR dysglycaemi*[tiab] OR hyperinsulinism[MeSH] OR hyperinsulin*[tiab] OR “Diabetes, Gestational”[Mesh] OR (gestation*[tiab] AND diabet*[tiab]) OR (“Maternal Nutritional Physiological Phenomena”[Mesh] AND diabet*[tiab])
#3 | | #1 AND #2
#4 | Limits | #3 NOT (“Animals”[Mesh] NOT (“Animals”[Mesh] AND “Humans”[Mesh])) NOT (editorial[ptyp] OR comment[ptyp] OR commentary[tiab] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic review[ptyp] OR systematic review[ti] OR meta-analysis[ptyp] OR meta-analysis[ti] OR meta-analyses[ti] OR protocol[ti] OR protocols[ti] OR retracted publication[ptyp] OR retraction of publication[ptyp] OR retraction of publication[tiab] OR retraction notice[ti] OR “retracted publication”[ti] OR “Congress”[Publication Type] OR “Consensus Development Conference”[Publication Type] OR “conference abstract*”[tiab] OR “conference proceeding*”[tiab] OR “conference paper*”[tiab] OR “practice guideline”[ptyp] OR “practice guideline”[ti]); Language: English; Publication date: from 2000/1/1 - 3000/12/12

[underlined: Database: Embase]

Provider: Elsevier

Date(s) Searched: July 5, 2022 (initial search); July 5, 2022 – January 9, 2024 (continuous evidence monitoring)

Dates Covered: January 1, 2000 – January 9, 2024

Table A 3 Search for Embase

Search # | Concept | String
#1 | Beverages | ‘Beverages’/de OR ‘sweetened beverage’/exp OR ‘Drinking Water’/exp OR ‘Carbonated Beverages’/exp OR ‘carbonated water’/exp OR ‘Energy Drink’/exp OR ‘Fruit and Vegetable Juice’/exp OR ‘Coffee’/exp OR ‘Tea’/exp OR ‘Milk’/de OR ‘soybean milk’/exp OR ‘Buttermilk’/exp OR ‘diet drink*’:ab,ti OR ‘sweetening agent*’:ab,ti OR ‘artificially sweet*’:ab,ti OR ‘beverage’:ab,ti OR ‘beverages’:ab,ti OR ‘sports drink*’:ab,ti OR ‘fortified drink*’:ab,ti OR ‘sweetened drink*’:ab,ti OR ‘sweet drink*’:ab,ti OR ‘sugary drink*’:ab,ti OR ‘dairy drink*’:ab,ti OR ‘chocolate drink*’:ab,ti OR smoothie*:ab,ti OR ‘carbonated drink*’:ab,ti OR ‘soft drink*’:ab,ti OR ‘soda’:ab,ti OR ‘sodas’:ab,ti OR ‘caffeinated drink*’:ab,ti OR ‘drinking water’:ab,ti OR ‘bottled water’:ab,ti OR ‘carbonated water’:ab,ti OR ‘sparkling water’:ab,ti OR ‘flavored water’:ab,ti OR ‘flavoured water’:ab,ti OR ‘flavoured drink’:ab,ti OR ‘flavored drink*’:ab,ti OR ‘energy drink*’:ab,ti OR ‘juice’:ab,ti OR ‘juices’:ab,ti OR ‘fruit drink*’:ab,ti OR ‘fizzy drink*’:ab,ti OR ‘coffee’:ab,ti OR ‘tea’:ab,ti OR ‘milk’:ab,ti OR ‘soymilk’:ab,ti OR ‘soy milk’:ab,ti OR ‘buttermilk’:ab,ti OR ‘liquid’:ab,ti OR ‘liquids’:ab,ti
#2 | Type two diabetes | ‘Diabetes Mellitus’/de OR ‘diabetic obesity’/exp OR ‘impaired glucose tolerance’/exp OR ‘non insulin dependent diabetes mellitus’/exp OR ‘insulin resistance’/exp OR ‘Hypoglycemia’/exp OR ‘glucose blood level’/exp OR ‘hyperinsulinism’/exp OR ‘pregnancy diabetes mellitus’/exp OR ‘type 2 diabet*’:ab,ti OR ‘T2D’:ab,ti OR ‘adult onset diabetes’:ab,ti OR ‘prediabet*’:ab,ti OR ‘pre diabet*’:ab,ti OR ‘insulin resistance’:ab,ti OR ‘insulin resistant’:ab,ti OR ‘glucose intolerance’:ab,ti OR ‘glucose intolerant’:ab,ti OR ‘glucose tolerance’:ab,ti OR ‘glucose tolerant’:ab,ti OR ‘hemoglobin A1c’:ab,ti OR ‘hba1c’:ab,ti OR ‘hba 1c’:ab,ti OR ‘haemoglobin A1c’:ab,ti OR ‘hyperglycemia’:ab,ti OR ‘hyperglycaemia’:ab,ti OR ‘hypoglycemia’:ab,ti OR ‘hypoglycaemia’:ab,ti OR ((‘impaired’ OR ‘glucose’) NEAR/4 ‘fasting’):ab,ti OR ‘blood glucose’:ab,ti OR ‘plasma glucose’:ab,ti OR ‘serum glucose’:ab,ti OR ‘glycemi*’:ab,ti OR glycaemi*:ab,ti OR ‘blood sugar’:ab,ti OR dysglycemi*:ab,ti OR dysglycaemi*:ab,ti OR hyperinsulin*:ab,ti OR (‘gestation*’ NEAR/4 ‘diabet*’):ab,ti OR (‘maternal nutrition’/exp AND ‘diabet*’:ab,ti)
#3 | | #1 AND #2
#4 | Limits | #3 AND ([article]/lim OR [article in press]/lim) NOT ([animals]/lim NOT ([animals]/lim AND [humans]/lim)) AND [english]/lim NOT ([conference abstract]/lim OR [conference paper]/lim OR [conference review]/lim OR [editorial]/lim OR [erratum]/lim OR [letter]/lim OR [note]/lim OR ‘retraction of publication’:ab,ti OR ‘retraction notice’:ti OR ‘retracted publication’:ab,ti OR [review]/lim OR [systematic review]/lim OR [meta analysis]/lim OR ‘practice guideline’:ti) AND [2000-2024]/py

[underlined: Database: Cochrane Central Register of Controlled Trials (CENTRAL)]

Provider: John Wiley & Sons

Date(s) Searched: July 5, 2022 (initial search); July 5, 2022 – January 9, 2024 (continuous evidence monitoring)

Dates Covered: January 1, 2000 – January 9, 2024

Table A 4 Search for Cochrane CENTRAL

Search # | Concept | String
#1 | Beverages | [mh ^“Beverages”] OR [mh “Sugar Sweetened Beverages”] OR [mh “Artificially Sweetened Beverages”] OR [mh “Drinking Water”] OR [mh “Carbonated Beverages”] OR [mh “Energy Drinks”] OR [mh “Fruit and Vegetable Juices”] OR [mh “Coffee”] OR [mh “Tea”] OR [mh ^“Milk”] OR [mh “Soy Milk”] OR [mh “Buttermilk”] OR (“diet drink*” OR “sweetening agent*” OR “artificially sweet*” OR beverage OR beverages OR “sports drink*” OR “fortified drink*” OR “sweetened drink*” OR “sweet drink*” OR “sugary drink*” OR “dairy drink*” OR “chocolate drink*” OR smoothie* OR “carbonated drink*” OR “soft drink*” OR soda OR sodas OR “caffeinated drink*” OR “drinking water” OR “bottled water” OR “carbonated water” OR “sparkling water” OR “flavored water” OR “flavoured water” OR “flavoured drink” OR “flavored drink*” OR “energy drink*” OR juice OR juices OR “fruit drink*” OR “fizzy drink*” OR coffee OR tea OR milk OR soymilk OR “soy milk” OR buttermilk OR liquid OR liquids):ti,ab,kw
#2 | Type two diabetes | [mh ^“Diabetes Mellitus”] OR [mh “Diabetes Mellitus, Type 2”] OR [mh “Prediabetic State”] OR [mh “Insulin Resistance”] OR [mh “Hyperglycemia”] OR [mh “Glycated Hemoglobin A”] OR [mh “Hypoglycemia”] OR [mh “blood glucose”] OR [mh hyperinsulinism] OR [mh “Diabetes, Gestational”] OR (“type 2 diabet*” OR “T2D” OR “adult onset diabetes” OR “prediabet*” OR “pre diabet*” OR “insulin resistance” OR “insulin resistant” OR “glucose intolerance” OR “glucose intolerant” OR “glucose tolerance” OR “glucose tolerant” OR “hemoglobin A1c” OR “hba1c” OR “hba 1c” OR “haemoglobin A1c” OR “hyperglycemia” OR hyperglycaemia OR “hypoglycemia” OR “hypoglycaemia” OR ((impaired OR glucose) AND fasting) OR “blood glucose” OR “plasma glucose” OR “serum glucose” OR “glycemi*” OR glycaemi* OR “blood sugar” OR dysglycemi* OR dysglycaemi* OR hyperinsulin*):ti,ab,kw
#3 | | #1 AND #2; In Trials, word variations searched; Year First Published: 2000-2024

[underlined: Database: CINAHL]

Provider: EBSCO

Date(s) Searched: July 5, 2022 (initial search); July 5, 2022 – January 9, 2024 (continuous evidence monitoring)

Dates Covered: January 1, 2000 – January 9, 2024

Table A 5 Search for CINAHL

Search # | Concept | String
#1 | Beverages | (MH “Beverages”) OR MH (“Sweetened Beverages”) OR (MH “Water+”) OR (MH “Carbonated Beverages”) OR (MH “Energy Drinks”) OR (MH “Fruit Juices”) OR (MH “Coffee”) OR (MH “Tea”) OR (MH “Milk”) OR (MH “Milk Substitutes+”) OR TI (diet drink* OR sweetening agent* OR artificially sweet* OR beverage* OR sports drink* OR fortified drink* OR sweetened drink* OR sweet drink* OR sugary drink* OR dairy drink* OR chocolate drink* OR smoothie* OR carbonated drink* OR soft drink* OR soda OR sodas OR caffeinated drink* OR drinking water OR bottled water OR carbonated water OR sparkling water OR flavored water OR flavoured water OR flavoured drink* OR flavored drink* OR energy drink* OR juice OR juices OR fruit drink* OR fizzy drink* OR coffee OR tea OR milk OR soymilk OR buttermilk OR liquid OR liquids) OR AB (diet drink* OR sweetening agent* OR artificially sweet* OR beverage* OR sports drink* OR fortified drink* OR sweetened drink* OR sweet drink* OR sugary drink* OR dairy drink* OR chocolate drink* OR smoothie* OR carbonated drink* OR soft drink* OR soda OR sodas OR caffeinated drink* OR drinking water OR bottled water OR carbonated water OR sparkling water OR flavored water OR flavoured water OR flavoured drink* OR flavored drink* OR energy drink* OR juice OR juices OR fruit drink* OR fizzy drink* OR coffee OR tea OR milk OR soymilk OR buttermilk OR liquid OR liquids)
#2 | Type two diabetes | (MH “Diabetes Mellitus”) OR (MH “Diabetes Mellitus, Type 2”) OR (MH “Diabetes Mellitus, Gestational”) OR (MH “Prediabetic State”) OR (MH “Insulin Resistance+”) OR (MH “Hyperglycemia+”) OR (MH “Hemoglobin A, Glycosylated”) OR (MH “Hypoglycemia+”) OR (MH “blood glucose”) OR (MH “hyperinsulinism+”) OR (TI “type 2 diabet*” OR “T2D” OR “adult onset diabetes” OR “prediabet*” OR “pre diabet*” OR “insulin resistance” OR “insulin resistant” OR “glucose intolerance” OR “glucose intolerant” OR “glucose tolerance” OR “glucose tolerant” OR “hemoglobin A1c” OR “hba1c” OR “hba 1c” OR “haemoglobin A1c” OR “hyperglycemia” OR hyperglycaemia OR “hypoglycemia” OR “hypoglycaemia” OR ((impaired OR glucose) N4 fasting) OR “blood glucose” OR “plasma glucose” OR “serum glucose” OR “glycemi*” OR glycaemi* OR “blood sugar” OR dysglycemi* OR dysglycaemi* OR hyperinsulin* OR (gestation* N4 diabet*)) OR (AB “type 2 diabet*” OR “T2D” OR “adult onset diabetes” OR “prediabet*” OR “pre diabet*” OR “insulin resistance” OR “insulin resistant” OR “glucose intolerance” OR “glucose intolerant” OR “glucose tolerance” OR “glucose tolerant” OR “hemoglobin A1c” OR “hba1c” OR “hba 1c” OR “haemoglobin A1c” OR “hyperglycemia” OR hyperglycaemia OR “hypoglycemia” OR “hypoglycaemia” OR ((impaired OR glucose) N4 fasting) OR “blood glucose” OR “plasma glucose” OR “serum glucose” OR “glycemi*” OR glycaemi* OR “blood sugar” OR dysglycemi* OR dysglycaemi* OR hyperinsulin* OR (gestation* N4 diabet*)) OR ((MH “Maternal Nutritional Physiology”) AND ((TI diabet*) OR (AB diabet*)))
#3 | | S1 AND S2
#4 | Limits | #3 NOT ((MH “Animals+”) OR (MH “Animal Studies”)); NOT ((MH “Literature Review”) OR (MH “Meta Analysis”) OR (MH “Systematic Review”) OR (MH “News”) OR (MH “Retracted Publication”) OR (MH “Retraction of Publication); Limiters - English Language, Expanders - Apply equivalent subject, Published Date: 20000101-20240109