# Appendix 1 Abbreviations

Table A 1 List of abbreviations
Abbreviation: Full name
BMI: Body Mass Index
CNPP: Center for Nutrition Policy and Promotion
HbA1C: Hemoglobin A1C
HDI: Human Development Index
HHS: United States Department of Health and Human Services
HOMA-IR: Homeostatic Model Assessment for Insulin Resistance
LNCSB: Low- and No-Calorie Sweetened Beverage(s)
NESR: Nutrition Evidence Systematic Review
NGAD: Nutrition Guidance and Analysis Division
NIH: National Institutes of Health
RCT: Randomized Controlled Trial
USDA: United States Department of Agriculture