# References of the articles included in the systematic review

### Children and adolescents

1 Ambrosini GL, Oddy WH, Huang RC, Mori TA, Beilin LJ, Jebb SA. Prospective associations between sugar-sweetened beverage intakes and cardiometabolic risk factors in adolescents. Am J Clin Nutr. Aug 2013;98(2):327–34. doi:10.3945/ajcn.112.051383 23719557
2 Mirmiran P, Yuzbashian E, Asghari G, Hosseinpour-Niazi S, Azizi F. Consumption of sugar sweetened beverage is associated with incidence of metabolic syndrome in Tehranian children and adolescents. Nutr Metab (Lond). 2015;12:25. doi:10.1186/s12986-015-0021-6 26225136
3 Cohen CC, Dabelea D, Michelotti G, . Metabolome alterations linking sugar-sweetened beverage intake with dyslipidemia in youth: The Exploring Perinatal Outcomes Among Children (EPOCH) study. Metabolites. Jun 17 2022;12(6)doi:10.3390/metabo12060559
4 Della Corte KA, Penczynski K, Kuhnle G, . The prospective association of dietary sugar intake in adolescence with risk markers of type 2 diabetes in young adulthood. Front Nutr. 2020;7:615684. doi:10.3389/fnut.2020.615684 33537338
5 Goletzke J, Herder C, Joslowski G, . Habitually higher dietary glycemic index during puberty is prospectively related to increased risk markers of type 2 diabetes in younger adulthood. Diabetes Care. Jul 2013;36(7):1870–6. doi:10.2337/dc12-2063 23349549

### Adults and older adults

6 Bazzano LA, Li TY, Joshipura KJ, Hu FB. Intake of fruit, vegetables, and fruit juices and risk of diabetes in women. Diabetes Care. Jul 2008;31(7):1311–7. doi:10.2337/dc08-0080 18390796
7 Bhupathiraju SN, Pan A, Malik VS, . Caffeinated and caffeine-free beverages and risk of type 2 diabetes. Am J Clin Nutr. Jan 2013;97(1):155–66. doi:10.3945/ajcn.112.048603 23151535
8 Campos V, Despland C, Brandejsky V, . Sugar- and artificially sweetened beverages and intrahepatic fat: A randomized controlled trial. Obesity (Silver Spring). Dec 2015;23(12):2335–9. doi:10.1002/oby.21310 26727115
9 Canhada SL, Vigo A, Levy R, . Association between ultra-processed food consumption and the incidence of type 2 diabetes: the ELSA-Brasil cohort. Diabetol Metab Syndr. Nov 15 2023;15(1):233. doi:10.1186/s13098-023-01162-2 37968763
10 Chen Z, Khandpur N, Desjardins C, . Ultra-processed food consumption and risk of type 2 diabetes: Three large prospective U.S. cohort studies. Diabetes Care. Jul 1 2023;46(7):1335–1344. doi:10.2337/dc22-1993 36854188
11 Cho Y, Ryu S, Kim R, Shin MJ, Oh H. Ultra-processed Food Intake and Risk of Type 2 Diabetes in Korean Adults. J Nutr. Jan 2024;154(1):243–251. doi:10.1016/j.tjnut.2023.11.021 38007182
12 de Koning L, Malik VS, Rimm EB, Willett WC, Hu FB. Sugar-sweetened and artificially sweetened beverage consumption and risk of type 2 diabetes in men. Am J Clin Nutr. Jun 2011;93(6):1321–7. doi:10.3945/ajcn.110.007922 21430119
13 Drouin-Chartier JP, Zheng Y, Li Y, . Changes in consumption of sugary beverages and artificially sweetened beverages and subsequent risk of type 2 diabetes: Results from three large prospective U.S. cohorts of women and men. Diabetes Care. Dec 2019;42(12):2181–2189. doi:10.2337/dc19-0734 31582428
14 Ebbeling CB, Feldman HA, Steltz SK, Quinn NL, Robinson LM, Ludwig DS. Effects of sugar-sweetened, artificially sweetened, and unsweetened beverages on cardiometabolic risk factors, body composition, and sweet taste preference: A randomized controlled trial. J Am Heart Assoc. Aug 4 2020;9(15):e015668. doi:10.1161/JAHA.119.015668 32696704
15 Engel S, Tholstrup T, Bruun JM, Astrup A, Richelsen B, Raben A. Effect of high milk and sugar-sweetened and non-caloric soft drink intake on insulin sensitivity after 6 months in overweight and obese adults: a randomized controlled trial. Eur J Clin Nutr. Mar 2018;72(3):358–366. doi:10.1038/s41430-017-0006-9 29235560
16 Ericson U, Hindy G, Drake I, . Dietary and genetic risk scores and incidence of type 2 diabetes. Genes Nutr. 2018;13:13. doi:10.1186/s12263-018-0599-1 29796113
17 Eshak ES, Iso H, Mizoue T, Inoue M, Noda M, Tsugane S. Soft drink, 100% fruit juice, and vegetable juice intakes and risk of diabetes mellitus. Clin Nutr. Apr 2013;32(2):300–8. doi:10.1016/j.clnu.2012.08.003 22917499
18 Fagherazzi G, Vilier A, Saes Sartorelli D, Lajous M, Balkau B, Clavel-Chapelon F. Consumption of artificially and sugar-sweetened beverages and incident type 2 diabetes in the Etude Epidemiologique aupres des femmes de la Mutuelle Generale de l’Education Nationale-European Prospective Investigation into Cancer and Nutrition cohort. Am J Clin Nutr. Mar 2013;97(3):517–23. doi:10.3945/ajcn.112.050997 23364017
19 Gardener H, Moon YP, Rundek T, Elkind MSV, Sacco RL. Diet soda and sugar-sweetened soda consumption in relation to incident diabetes in the Northern Manhattan Study. Curr Dev Nutr. May 2018;2(5):nzy008. doi:10.1093/cdn/nzy008 29955723
20 Greenberg JA, Axen KV, Schnoll R, Boozer CN. Coffee, tea and diabetes: the role of weight loss and caffeine. Int J Obes (Lond). Sep 2005;29(9):1121–9. doi:10.1038/sj.ijo.0802999 15925959
21 Hernandez-Cordero S, Barquera S, Rodriguez-Ramirez S, . Substituting water for sugar-sweetened beverages reduces circulating triglycerides and the prevalence of metabolic syndrome in obese but not in overweight Mexican women in a randomized controlled trial. J Nutr. Nov 2014;144(11):1742–52. doi:10.3945/jn.114.193490 25332472
22 Hirahatake KM, Jacobs DR, Shikany JM, . Cumulative intake of artificially sweetened and sugar-sweetened beverages and risk of incident type 2 diabetes in young adults: the Coronary Artery Risk Development In Young Adults (CARDIA) Study. Am J Clin Nutr. Sep 1 2019;110(3):733–741. doi:10.1093/ajcn/nqz154 31374564
23 Huang M, Quddus A, Stinson L, . Artificially sweetened beverages, sugar-sweetened beverages, plain water, and incident diabetes mellitus in postmenopausal women: the prospective Women’s Health Initiative observational study. Am J Clin Nutr. Aug 2017;106(2):614–622. doi:10.3945/ajcn.116.145391 28659294
24 Imamura F, Schulze MB, Sharp SJ, . Estimated substitution of tea or coffee for sugar-sweetened beverages was associated with lower type 2 diabetes incidence in case-cohort analysis across 8 European countries in the EPIC-InterAct Study. J Nutr. Nov 1 2019;149(11):1985–1993. doi:10.1093/jn/nxz156 31396627
25 InterAct C, Romaguera D, Norat T, . Consumption of sweet beverages and type 2 diabetes incidence in European adults: results from EPIC-InterAct. Diabetologia. Jul 2013;56(7):1520–30. doi:10.1007/s00125-013-2899-8 23620057
26 Jahromi MK, Farhadnejad H, Teymoori F, . Adherence to diet with higher dietary diabetes risk reduction score is associated with reduced risk of type 2 diabetes incident in Iranian adults. BMC Public Health. Jun 14 2023;23(1):1144. doi:10.1186/s12889-023-16024-9 37316867
27 Kendig MD, Chow JYL, Martire SI, Rooney KB, Boakes RA. Switching from sugar- to artificially-sweetened beverages: A 12-week trial. Nutrients. May 4 2023;15(9)doi:10.3390/nu15092191
28 McNaughton SA, Mishra GD, Brunner EJ. Dietary patterns, insulin resistance, and incidence of type 2 diabetes in the Whitehall II Study. Diabetes Care. Jul 2008;31(7):1343–8. doi:10.2337/dc07-1946 18390803
29 Montonen J, Jarvinen R, Knekt P, Heliovaara M, Reunanen A. Consumption of sweetened beverages and intakes of fructose and glucose predict type 2 diabetes occurrence. J Nutr. Jun 2007;137(6):1447–54. doi:10.1093/jn/137.6.1447 17513405
30 Nettleton JA, Lutsey PL, Wang Y, Lima JA, Michos ED, Jacobs DR, Jr. Diet soda intake and risk of incident metabolic syndrome and type 2 diabetes in the Multi-Ethnic Study of Atherosclerosis (MESA). Diabetes Care. Apr 2009;32(4):688–94. doi:10.2337/dc08-1799 19151203
31 O’Connor L, Imamura F, Lentjes MA, Khaw KT, Wareham NJ, Forouhi NG. Prospective associations and population impact of sweet beverage intake and type 2 diabetes, and effects of substitutions with alternative beverages. Diabetologia. Jul 2015;58(7):1474–83. doi:10.1007/s00125-015-3572-1 25944371
32 Odegaard AO, Koh WP, Arakawa K, Yu MC, Pereira MA. Soft drink and juice consumption and risk of physician-diagnosed incident type 2 diabetes: the Singapore Chinese Health Study. Am J Epidemiol. Mar 15 2010;171(6):701–8. doi:10.1093/aje/kwp452 20160170
33 Olsson K, Ramne S, Gonzalez-Padilla E, Ericson U, Sonestedt E. Associations of carbohydrates and carbohydrate-rich foods with incidence of type 2 diabetes. Br J Nutr. Oct 14 2021;126(7):1065–1075. doi:10.1017/S0007114520005140 33355062
34 Palmer JR, Boggs DA, Krishnan S, Hu FB, Singer M, Rosenberg L. Sugar-sweetened beverages and incidence of type 2 diabetes mellitus in African American women. Arch Intern Med. Jul 28 2008;168(14):1487–92. doi:10.1001/archinte.168.14.1487 18663160
35 Pan A, Malik VS, Schulze MB, Manson JE, Willett WC, Hu FB. Plain-water intake and risk of type 2 diabetes in young and middle-aged women. Am J Clin Nutr. Jun 2012;95(6):1454–60. doi:10.3945/ajcn.111.032698 22552035
36 Paynter NP, Yeh HC, Voutilainen S, . Coffee and sweetened beverage consumption and the risk of type 2 diabetes mellitus: the atherosclerosis risk in communities study. Am J Epidemiol. Dec 1 2006;164(11):1075–84. doi:10.1093/aje/kwj323 16982672
37 Ramne S, Drake I, Ericson U, . Identification of Inflammatory and Disease-Associated Plasma Proteins that Associate with Intake of Added Sugar and Sugar-Sweetened Beverages and Their Role in Type 2 Diabetes Risk. Nutrients. Oct 14 2020;12(10)doi:10.3390/nu12103129
38 Rhee JJ, Mattei J, Hughes MD, Hu FB, Willett WC. Dietary diabetes risk reduction score, race and ethnicity, and risk of type 2 diabetes in women. Diabetes Care. Apr 2015;38(4):596–603. doi:10.2337/dc14-1986 25592193
39 Rose BD, Rimm EB, Zhang X, . You are What You Drink? How Associations Between Profiles of Beverage Consumption and Type 2 Diabetes Risk are Mediated by Biomarker Networks. Am J Clin Nutr. Jul 2023;118(1):68–76. doi:10.1016/j.ajcnut.2023.04.015 37061165
40 Sakurai M, Nakamura K, Miura K, . Sugar-sweetened beverage and diet soda consumption and the 7-year risk for type 2 diabetes mellitus in middle-aged Japanese men. Eur J Nutr. Feb 2014;53(1):251–8. doi:10.1007/s00394-013-0523-9 23575771
41 Schulze MB, Manson JE, Ludwig DS, . Sugar-sweetened beverages, weight gain, and incidence of type 2 diabetes in young and middle-aged women. JAMA. Aug 25 2004;292(8):927–34. doi:10.1001/jama.292.8.927 15328324
42 Srour B, Fezeu LK, Kesse-Guyot E, . Ultraprocessed Food Consumption and Risk of Type 2 Diabetes Among Participants of the NutriNet-Sante Prospective Cohort. JAMA Intern Med. Feb 1 2020;180(2):283–291. doi:10.1001/jamainternmed.2019.5942 31841598
43 Stern D, Mazariegos M, Ortiz-Panozo E, . Sugar-Sweetened Soda Consumption Increases Diabetes Risk Among Mexican Women. J Nutr. May 1 2019;149(5):795–803. doi:10.1093/jn/nxy298 31050751
44 Tate DF, Turner-McGrievy G, Lyons E, . Replacing caloric beverages with water or diet beverages for weight loss in adults: main results of the Choose Healthy Options Consciously Everyday (CHOICE) randomized clinical trial. Am J Clin Nutr. Mar 2012;95(3):555–63. doi:10.3945/ajcn.111.026278 22301929
45 Teshima N, Shimo M, Miyazawa K, . Effects of sugar-sweetened beverage intake on the development of type 2 diabetes mellitus in subjects with impaired glucose tolerance: the Mihama diabetes prevention study. J Nutr Sci Vitaminol (Tokyo). 2015;61(1):14–9. doi:10.3177/jnsv.61.14 25994135
46 Torres-Ibarra L, Rivera-Paredez B, Hernandez-Lopez R, . Regular consumption of soft drinks is associated with type 2 diabetes incidence in Mexican adults: findings from a prospective cohort study. Nutr J. Nov 20 2020;19(1):126. doi:10.1186/s12937-020-00642-9 33218344
47 Viana Dias JP, Pimenta AM, de Souza Costa Sobrinho P, Miranda Hermsdorff HH, Bressan J, Nobre LN. Consumption of sweetened beverages is associated with the incidence of type 2 diabetes in Brazilian adults (CUME project). Nutr Metab Cardiovasc Dis. Apr 2023;33(4):789–796. doi:10.1016/j.numecd.2023.01.022 36849319
48 von Ruesten A, Feller S, Bergmann MM, Boeing H. Diet and risk of chronic diseases: results from the first 8 years of follow-up in the EPIC-Potsdam study. Eur J Clin Nutr. Apr 2013;67(4):412–9. doi:10.1038/ejcn.2013.7 23388667