# Summary of conclusion statements and grades

The Committee answered the systematic review question, “What is the relationship between sugar-sweetened beverage consumption and risk of type 2 diabetes?”, with the following conclusion statements.^*^ The grades reflect the strength of the evidence underlying the conclusion statements.

* A conclusion statement is carefully constructed, based on the evidence reviewed, to answer the systematic review question. A conclusion statement does not draw implications and should not be interpreted as dietary guidance.

### Infants and young children

A conclusion statement cannot be drawn about the relationship between sugar-sweetened beverage consumption by infants and young children up to age 24 months and risk of type 2 diabetes because there is no evidence available. (Grade: Grade Not Assignable)

### Children and adolescents

A conclusion statement cannot be drawn about the relationship between sugar-sweetened beverage consumption by children and adolescents and risk of type 2 diabetes because of substantial concerns with directness in the body of evidence. (Grade: Grade Not Assignable)

### Adults and older adults

Sugar-sweetened beverage consumption by adults and older adults may be associated with higher risk of type 2 diabetes. This conclusion statement is based on evidence graded as moderate. (Grade: Moderate)

## Research recommendations

The Committee identified the following research recommendations that describe the research, data, and methodological advances that are needed to strengthen the body of evidence on sugar-sweetened beverage consumption and risk of type 2 diabetes.

1. Examine sugar-sweetened beverage intake in childhood (from birth to adolescence) in relation to changes in risk of type 2 diabetes across a range of ages and life stages.
2. Conduct well-controlled, randomized interventions, particularly in the United States with diverse populations, to examine the effect of sugar-sweetened beverage consumption and risk of type 2 diabetes.
3. Include diverse populations with varying race and/or ethnicity and socioeconomic position.
4. Control for confounding factors, such as family history of diabetes, that may impact the relationship between sugar-sweetened beverage consumption and risk of type 2 diabetes.
5. Provide repeated measures of beverage intake using validated dietary assessment tools and methods throughout the course of follow-up.
6. Use clear, specific definitions for sugar-sweetened beverages, particularly to differentiate from low- and no-calorie sweetened beverages.

Table 8 Evidence examining the relationship between sugar-sweetened beverage consumption in children and adolescents and risk of type 2 diabetes^a^

Study and Participant Characteristics | Intervention or Exposure, Comparator, and Outcome(s) | Results | Methodological Considerations
Ambrosini, 2013 ^1^; PCS, Western Australian Pregnancy Cohort (Raine) Study, Australia; Analytic N=1124 (glucose); 1083 (insulin, HOMA-IR); Study objective: To test the hypothesis that higher SSB intakes are associated with increases in cardiometabolic risk factors between 14 and 17y of age; Participant characteristics at baseline: adolescents; - Age (mean and/or range): 14 (0.2)y; - Female: 49%; - Race and/or ethnicity: NR; - Socioeconomic position: 35% low maternal education (≤10y); - Anthropometry: BMI ~21 (4) kg/m^2^; 22% with overweight or obesity; - Physical activity: ~111 (30) watts on bicycle ergometer working capacity test; - Family history of diabetes: NR; - Smoking: NR; - TEI: NR; - Beverage intake at baseline: ~300 g/d SSB; 89% were SSB consumers; Excluded from study or analysis: participants who reported not fasting before venipuncture | Exposure: Carbonated soft drinks (excluding artificially sweetened or diet beverages), cordials or squash (fruit drink concentrate), and fruit juice drinks (excluding 100% juice); - Serving Size: 1 cup (250mL or 8.45oz) or 261g; Comparator: categorical intake (tertiles of svg/d); - Tertile 1: 0 to 0.5 svg/d (0-130 g/d); - Tertile 2: >0.5 to 1.3 svg/d (130-329 g/d); - Tertile 3: >1.3 svg/d (331-2876 g/d); Assessment methods and timing:; - FFQ assessing usual intake over previous year; completed by parents at 14y and adolescents at 17y; - Baseline (14y), 3y follow-up (17y); Outcome assessment methods and timing:; - Fasting blood samples were collected and HOMA-IR was calculated; - Baseline (14y), 3y follow-up (17y) | [underlined: Change in fasting serum glucose (mmol/L) between 14-17y with each tertile increase in SSB intake], β (95% CI); Girls; Tertile 1: REF; Tertile 2: 0.1 (−1.3, 1.5), p=0.89; Tertile 3: −1.2 (−3.0, 0.5), p=0.17; P-trend=0.22; Boys; Tertile 1: REF; Tertile 2: −0.5 (−2.0, 1.0), p=0.50; Tertile 3: −0.5 (−2.1, 1.1), p=0.55; P-trend=0.55; [underlined: Change in fasting serum insulin (mIU/L) between 14-17y with each tertile increase in SSB intake], β (95% CI); Girls; Tertile 1: REF; Tertile 2: 1.1 (−6.6, 8.8), P=0.79; Tertile 3: −4.5 (−13.8, 4.9), P=0.35; P-trend=0.42; Boys; Tertile 1: REF; Tertile 2: 0.2 (−8.2, 8.6), P=0.97; Tertile 3: −1.4 (−10.3, 7.4), P=0.75; P-trend=0.74; [underlined: Change in HOMA-IR between 14-17y with each tertile increase in SSB intake], β (95% CI); Girls; Tertile 1: REF; Tertile 2: −1.4 (−17.6, 14.7), P=.86; Tertile 3: −18.1 (−37.7, 1.5), P=0.07; P-trend=0.42; Boys; Tertile 1: REF; Tertile 2: −3.5 (−20.6, 13.6), P=0.69; Tertile 3: −7.8 (−25.8, 10.2), P=0.39; P-trend=0.40 | Model adjustments:; - TEI: no; - Key confounders: sex, age, socioeconomic position (maternal education, family income), anthropometry, physical activity; - Other: pubertal stage, dietary misreporting, ‘Healthy’ and ‘Western’ dietary pattern scores; Limitations:; - Did not account for key confounders: race and/or ethnicity, family history of diabetes; - No evidence whether the result was biased due to missing data; - No preregistered data analysis plan; Funding:; National Heart Foundation of Australia and Beyond Blue Cardiovascular Disease and Depression Strategic Research Program; Australian National Health and Medical Research Council; UK Medical Research Council
Cohen, 2022 ^3^; PCS, EPOCH (Exploring Perinatal Outcomes among CHildren Study), U.S.; Analytic N=597; Study objective: To assess intermediary metabolic alterations that link sugar-sweetened beverage intake to cardiometabolic risk factors in youth; Participant characteristics at baseline: children; - Age (mean and/or range): Mean ~10.4 (1.5)y; - Female: 50%; - Race and/or ethnicity: 48% Non-Hispanic White; 8% Non-Hispanic Black; 6% Non-Hispanic Other; 39% Hispanic; - Socioeconomic position: NR; - Anthropometry: BMIz 0.19-0.37 (NS difference between quartiles); - Physical activity: NR; - Family history of diabetes: 17% in utero GDM exposure; - Smoking: NR; - TEI: ~1775 kcal/d; - Beverage intake at baseline: SSB intake for quartiles ranged from 0.11 (0.09) to 1.86 (0.91) svg/d; Excluded from study or analysis: missing data | Exposure: SSB, including sodas, fruit drinks (i.e., Sunny Delight, Hawaiian Punch, etc.), sports drinks (i.e., Gatorade), and sweetened tea or coffee; - Serving Size: NR; Comparator: categorical intake (quartiles of svg/d); Median energy-adjusted intakes (svg/d) in each quartile as continuous variable; - Quartile 1: 0-0.25; - Quartile 2: 0.26-0.54; - Quartile 3: 0.55-1.00; - Quartile 4: 1.01-5.12; Assessment methods and timing:; - FFQ assessing intake during the past week; - Baseline (~10y); Outcome assessment methods and timing:; - Fasting blood samples were collected and HOMA-IR was calculated; - Baseline (~10y), ~6y follow-up | [underlined: Change in fasting glucose (mg/dL) through adolescence by quartile of SSB intake during childhood], β (95% CI); Quartile 1: REF; Quartile 2: −0.7 (−4.1, 2.7); Quartile 3: −0.7 (−4.2, 2.7); Quartile 4: −1.4 (−4.9, 2.2); P-trend=0.488; [underlined: Change in fasting insulin (μIU/mL) through adolescence by quartile of SSB intake during childhood], β (95% CI); Quartile 1: REF; Quartile 2: −1.7 (−3.5, 0.1); Quartile 3: −1.1 (−2.9, 0.7); Quartile 4: −1.3 (−3.1, 0.6); P-trend=0.426; [underlined: Change in HOMA-IR through adolescence by quartile of SSB intake during childhood], β (95% CI); Quartile 1: REF; Quartile 2: −0.7 (−1.3, −0.1); Quartile 3: −0.4 (−1.0, 0.2); Quartile 4: −0.5 (−1.1, 0.1); P-trend=0.330; Analyses conducted for entire sample since no significant effect modification by sex (Pinteraction>0.10) | Model adjustments:; - TEI: yes, using residual method; - Key confounders: sex, age, race and/or ethnicity; - Other: none; Limitations:; - Did not account for key confounders: socioeconomic position, anthropometry, physical activity, family history of diabetes; - Exposure only assessed at baseline; - No evidence whether the result was biased due to missing data; - No preregistered data analysis plan; Funding:; NIDDK
Della Corte, 2020 ^4^; PCS, DONALD (DOrtmund Nutritional and Anthropometric Longitudinally Designed Study), Germany; Analytic N=254; Study objective: To examine the prospective relevance of dietary sugar intake (based on dietary data as well as urinary excretion data) in adolescent years for insulin sensitivity and biomarkers of inflammation in young adulthood.; Participant characteristics at baseline: children and adolescents; - Age (mean and/or range): 12y, 9-15y (females); 13y, 10-16y (males); - Female: 51%; - Race and/or ethnicity: NR; - Socioeconomic position: 57% paternal education ≤12y (female), 65% (male); - Anthropometry: 22% with overweight; BMI 17.8 kg/m^2^ (female), 18.8 kg/m^2^ (male); - Physical activity: NR; - Family history of diabetes: NR; - Smoking: 32% smoking in household; - TEI: 1,697 kcal (female); 2,151 kcal (male); - Beverage intake at baseline: % of total sugar from SSB: 4.5 (3.9) in males, 3.9 (3.7) in females; Excluded from study or analysis: fasting glucose concentrations <2.5 mmol/L threshold for calculating HOMA2-%S; nonsingleton, born preterm, or abnormal birthweight; missing data | Exposure: Total sugars from SSB (sweetened fruit juice drinks and nectars, soft drinks/soda, sweetened teas and water, instant beverages except dairy drinks, sweetened sports drinks) calculated as a percentage of TEI; - Serving Size: NR; Comparator: categorical intake (tertiles, g/d); - Tertile 1 (g/d): 9.3 (6.3, 12.0) in females; 8.6 (5.8, 12.5) in males; - Tertile 2 (g/d): 19.9 (17.0, 22.8) in females; 20.2 (18.6, 22.6) in males; - Tertile 3 (g/d): 33.4 (29.3, 24.3) in females; 32.3 (28.1, 38.3) in males; Assessment methods and timing:; - At least 2 (range 2-7, mean=6) 3d weighed food records; - Baseline (9-15y for females, 10-16y for males); Outcome assessment methods and timing:; - Fasting blood samples were collected and HOMA2-%S (the reciprocal of HOMA2-IR) was calculated.; - Adulthood (median 9y follow-up, 18-36y) | [underlined: Fasting plasma insulin (pmol/L) in adulthood], Mean (95% CI); Females; Tertile 1: 72.7 (63.7, 81.8); Tertile 2: 80.2 (71.7, 88.7); Tertile 3: 72.9 (63.5, 82.3); P-trend=0.66; Males; Tertile 1: 70.8 (59.1, 82.5); Tertile 2: 78.2 (66.9, 89.4); Tertile 3: 69.2 (58.1, 80.4); P-trend=0.85; [underlined: HOMA2-%S in adulthood], Mean (95% CI); Females; Tertile 1: 84.6 (76.9, 92.2); Tertile 2: 75.9 (68.7, 83.1); Tertile 3: 81.2 (73.2, 89.2); P-trend=0.70; Males; Tertile 1: 87.0 (76.3, 97.6); Tertile 2: 87.0 (76.3, 97.6); Tertile 3: 86.2 (76.1, 96.3); P-trend=0.79 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, socioeconomic position (paternal education), anthropometry; - Other: birth weight, gestational weight gain, smoking in the household, parental overweight, adult percent body fat; Limitations:; - Did not account for key confounders: race and/or ethnicity, physical activity, family history of diabetes; - Exposure only assessed at baseline; - No evidence whether the result was biased due to missing data; - No preregistered data analysis plan; Funding:; Ministry of Science and Research of North Rhine-Westphalia Germany; German Federal Ministry of Health; Ministry of Culture and Science of the State North Rhine-Westphalia; German Federal Ministry of Education and Research
Goletzke, 2013 ^5^; PCS, DONALD (DOrtmund Nutritional and Anthropometric Longitudinally Designed Study), Germany; Analytic N=226; Study objective: To examine whether the amount or the quality (dietary glycemic index, glycemic load, and added sugar, fiber, and whole-grain intake) of carbohydrates during puberty is associated with risk markers of T2D in younger adulthood; Participant characteristics at baseline: children and adolescents; - Age (mean and/or range): ~9.5y; 9-14y (female); 10-15y (male); - Female: 54%; - Race and/or ethnicity: NR; - Socioeconomic position: 47% maternal education ≥12y; 51% maternal occupation; - Anthropometry: 15% with overweight; - Physical activity: NR; - Family history of diabetes: NR; - Smoking: 34% smoking in household; - TEI: ~1870 kcal/d; - Beverage intake at baseline: added sugar from drinks as a % of energy by tertile of dietary glycemic index, T1: 3.2%; T2: 4.0%; T3: 6.1%; Excluded from study or analysis: non-singleton, born preterm, or abnormal birthweight (<2500 g); missing data; consistent underreporting of energy intake | Exposure: Added sugar from drinks calculated as a percentage of energy intake; - Serving Size: NR; Comparator: categorical intake (tertiles); Assessment methods and timing:; - Average of at least two 3d weighed food records (mean=5 records/participant); - Baseline (9-15y for females, 10-16y for males); Outcome assessment methods and timing:; - Fasting blood samples were collected and used to calculate HOMA-IR; - Adulthood (mean 22.7y, range 18-36y) | [underlined: HOMA-IR in adulthood], Mean (95% CI); Tertile 1: 2.60 (2.36, 2.86); Tertile 2: 2.43 (2.22, 2.65); Tertile 3: 2.40 (2.18, 2.63); P-trend=0.8; Data pooled for analysis since there were no differences by sex (P-interaction>0.02) | Model adjustments:; - TEI: yes, using residual method; - Key confounders: sex, age, socioeconomic position (maternal education), anthropometry; - Other: early life factors (firstborn), nutritional factors (carbohydrate, glycemic index, glycemic load, fiber, protein), waist circumference in younger adulthood; Limitations:; - Did not account for key confounders: race and/or ethnicity, physical activity, family history of diabetes; - Exposure only assessed at baseline; - High missing data; - No preregistered data analysis plan; Funding:; German Federal Ministry of Food, Agriculture, and Consumer Protection through the Federal Office for Agriculture and Food; Wereld Kanker Onderzoek Fonds; Ministry of Science and Research of North Rhine-Westphalia Germany
Mirmiran, 2015 ^2^; PCS, Tehran Lipid and Glucose Study, Iran; Analytic N=476; Study objective: To evaluate the association between SSB consumption with incident metabolic syndrome and its components 3.6 years later among children and adolescents in Iran; Participant characteristics at baseline: children and adolescents; - Age (mean and/or range): 13.6 (3.7)y; 6-18y; - Female: 68%; - Race and/or ethnicity: NR; - Socioeconomic position: 35% parental education level <12y; - Anthropometry: BMI ~19 (4) kg/m^2^; - Physical activity: NR; - Family history of diabetes: NR; - Smoking: NR; - TEI: 2116-3317 kcal/d (SSB quartile p-trend<0.001); - Beverage intake at baseline:; ○ SSB: 98 ml/d in boys, 70 ml/d in girls; ○ Sugar sweetened carbonated soft drinks: 38.5 (75.0) g/d; ○ Combined fruit juice drinks: 32.3 (60.1) g/d; Excluded from study or analysis: high fasting plasma glucose at baseline; missing data; energy intake to energy requirement ratios beyond ±3SD range | Exposure: SSB, including sugarsweetened carbonated soft drinks (“did not differentiate between artificial non-caloric sweeteners and those containing caloric sugar e.g. fructose or sucrose”) and combined fruit juice drinks (both 100% fruit juice and sugar sweetened synthetic juice drinks that are not 100% juice); - Serving Size: 1 cup (250mL); Comparator: categorical intake (quartiles); Median intakes (mL/d) in each quartile as continuous variable (SSB; Sugarsweetened carbonated soft drink; Combined fruit juice drinks); - Quartile 1: 9.3; 1.1; 1.3; - Quartile 2: 32.0; 9.3; 8.3; - Quartile 3: 58.6; 33.1; 20.4; - Quartile 4: 142.2; 100.0; 67.1; Assessment methods and timing:; - FFQ assessing usual intake over previous year (parent-assisted if needed); - Baseline; Outcome assessment methods and timing:; - Fasting blood samples were collected; high fasting plasma glucose defined as ≥100 mg/dL based on ADA recommendations or drug treatment in participants >18y after follow-up; - Baseline, ~3.6y follow-up | [underlined: Incident high fasting plasma glucose after 3.6y follow-up by baseline intake], OR (95% CI); SSB; Quartile 1: REF; Quartile 2: 1.21 (0.48, 3.21); Quartile 3: 1.87 (0.75, 4.68); Quartile 4: 1.95 (0.73, 5.22); P-trend=0.108; Sugar sweetened carbonated soft drinks; Quartile 1: REF; Quartile 2: 0.55 (0.20, 1.54); Quartile 3: 1.93 (0.83, 4.50); Quartile 4: 1.12 (0.40, 3.12); P-trend=0.251; Combined fruit juice drinks; Quartile 1: REF; Quartile 2: 1.13 (0.44, 2.91); Quartile 3: 0.64 (0.21, 1.92); Quartile 4: 1.19 (0.44, 3.21); P-trend: 0.947 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, anthropometry, physical activity, family history of diabetes; - Other: dietary fiber, tea and coffee, red and processed meat, fruit, vegetables; Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position; - Exposure subject to measurement error and only assessed at baseline; - No evidence whether the result was biased due to missing data; - No preregistered data analysis plan; Funding:; Research Institute for Endocrine Sciences at the Shahid Beheshti University of Medical Sciences

a Abbreviations: ADA: American Diabetes Association; ASB: artificial sweetened beverage(s); BMI: body mass index; BMIz: body mass index z-score; CI: confidence interval; d: day(s); dL: deciliter(s); FFQ: food frequency questionnaire; g: gram(s); HbA1c: hemoglobin A1C; HOMA-IR: homeostatic model assessment for insulin resistance; hr: hour; IAUC: incremental area under the curve; kcal: kilocalorie(s); kg: kilogram(s); L: liter(s); LNCSB: low- and no-calorie sweetened beverage(s); m: meter(s); mg: milligram(s); min: minute(s); mIU: milli international unit(s); mL: milliliter(s); N/A: not applicable; NIDDK: National Institute of Diabetes and Digestive and Kidney Diseases; nmol: nanomole(s); NR: not reported; NS: not significant; OGTT: oral glucose tolerance test; OR: odds ratio; PCS: prospective cohort study; REF: reference group; SSB: sugar-sweetened beverage(s); SD: standard deviation; SSB: sugar-sweetened beverage(s); svg: serving(s); T2D: type 2 diabetes; TEI: total energy intake; μIU: micro-international unit(s); μmol: micromole(s); wk: week(s); y: year(s)

Table 9 Risk of bias for observational studies examining sugar-sweetened beverage consumption in children and adolescents and risk of type 2 diabetes^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of reported result | Overall risk of bias
Ambrosini, 2013^1^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Cohen, 2022^3^ | HIGH | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Della Corte, 2020^4^ | HIGH | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Goletzke, 2013^5^ | HIGH | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Mirmiran, 2015^2^ | HIGH | HIGH | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH

a Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the “Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)” tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24). doi: 10.1016/j.envint.2024.108602. )

Table 10 Intervention studies examining the relationship between sugar-sweetened beverage consumption in adults and older adults and risk of type 2 diabetes^a^

Study and Participant Characteristics | Intervention, Comparator, and Outcome(s) | Results | Methodological Considerations
Campos, 2015 ^8^; RCT-Parallel, Switzerland; Baseline N=31, Analytic N=27 (Attrition: 13%); Study objective: To test the hypothesis that substituting artificially-sweetened beverages for SSB decreases intrahepatocellular lipid concentrations in subjects with overweight and high SSB consumption.; Participant characteristics at baseline: adults with overweight that habitually consume SSB; - Age (mean and/or range): 18-40y; - Female: 48%; - Race and/or ethnicity: NR; - Socioeconomic position: NR; - Anthropometry: BMI ~31 kg/m^2^; 52% with obesity; - Physical activity: ~9000 steps/d (sig diff between groups); - Family history of diabetes: NR; - Smoking: NR; - Alcohol intake: NR; - TEI: ~2300 kcal/d; - Beverage intake at baseline: All drank ≥44 oz/d of SSB; Excluded from study or analysis: BMI <25 kg/m^2^; consume fewer than two 22oz SSB a day | Intervention: SSB (n=13): Habitual intake of 2 or more 22oz servings of carbonated soft drinks and sugar-sweetened tea; every week participants were given new batch of SSB; - Serving Size: 660 mL (22oz); Comparator: LNCSB (n=14): replace habitual intake of SSB (2 or more 22oz servings of carbonated soft drinks and sugar-sweetened tea) with artificially sweetened beverages; every week participants were given new batch of ASBs; Duration: 12wk; Compliance: >90% for both groups based on returned packages; Outcome assessment methods and timing:; - Fasting blood samples were collected and used to calculate HOMA-IR; - Baseline (wk4), 12wk follow-up (wk16) | [underlined: Fasting plasma glucose (mmol/L)], Mean (SEM); Within group: Baseline, 12wk; LNCSB: 5.1 (0.1), 5.1 (0.1); SSB: 5.4 (0.1), 5.4 (0.1); Between groups: Change over 12wk; P=NS; [underlined: Fasting insulin (uU/mL)], Mean (SEM); Within group: Baseline, 12wk; LNCSB: 16.9 (2.1), 15.0 (2.2); SSB: 15.3 (2.2), 15.6 (2.0); Between groups: Change over 12wk; P=NS; [underlined: HOMA-IR], Mean (SEM); Within group: Baseline, 12wk; LNCSB: 4.1 (0.6), 3.6 (0.6); SSB: 3.7 (0.6), 4.0 (0.5); Between groups: Change over 12wk; P=NS | Model adjustments:; - TEI: yes (NS between-group differences at baseline or during study); Limitations:; - Methods for randomization and concealment NR; - Differences in attrition; - No power calculation; - Trial registry did not include data analysis plan; Funding:; Swiss National Foundation for Science; Fondation Raymond Berger pour la recherche sur le diabete et les maladies metaboliques (Lausanne, Switzerland)
Ebbeling, 2020 ^14^; RCT-Parallel, U.S.; Baseline N=203, Analytic N=186 (Attrition: 8%); Study objective: To compare effects of consuming SSB, artificially-sweetened beverages, and unsweetened beverages in adults who habitually consumed SSB; Participant characteristics at baseline: adults that habitually consume SSB; - Age (mean and/or range): ~27y; 18-40y; - Female: 40%; - Race and/or ethnicity: 51% White; 20% Black; 13% Asian; 17% Multiple/other/unknown; 12% Hispanic; - Socioeconomic position: 53% with bachelors degree or higher; 31% with some college, vocational school, or associate’s degree; 27% with household income ≥$60k/yr; - Anthropometry: BMI ~26 (5) kg/m^2^; - Physical activity: NR; - Family history of diabetes: NR; - Smoking: NR; - Alcohol intake: NR; - TEI: ~2100 (650) kcal/d; - Beverage intake at baseline: ~1.5 (1.3) svg/d (12-oz svg); Excluded from study or analysis: BMI <18.5 or >40 kg/m^2^; SSB consumption less than one 12-oz svg/d; FBG ≥110 mg/dL, physician diagnosis of a major medical or psychiatric illness; chronic use of any medication that could affect study outcomes; smoking >10 cigarettes/d; pregnancy (preceding 12mo) or plans to become pregnant during study period; lactation (preceding 3mo); change in hormonal contraceptives (preceding 3mo) | Intervention: SSB (n=60): participants instructed to drink SSB delivered to home and to not drink LNCSB; - Serving Size: 12oz; participants were instructed to drink delivered beverages at the same rate (number of svg/d) as usual SSB consumption; Comparator: Water (n=66): spring water, purified water, and unsweetened sparking water with or without flavoring; participants instructed to drink water delivered to home and to not drink SSB or LNCSB; LNCSB (n=60): artificially-sweetened/diet beverages; participants instructed to drink LNCSB delivered to home and to not drink SSB; Duration: 52wk; Compliance: Biweekly check-in telephone calls to review beverage consumption; NS difference between groups in number of beverage deliveries or check-in calls completed; Outcome assessment methods and timing:; - Fasting blood samples were collected and insulin sensitivity (as a % of value for a normal reference population) was evaluated by HOMA using glucose and insulin data; - Baseline, 52wk follow-up | [underlined: Change in fasting glucose (mg/dL) over 12mo], Mean (SE); Water: 1.8 (0.7), P=0.01; LNCSB: 0.9 (0.8), P=0.24; SSB: 1.8 (0.8), P=0.02; Between groups: P=0.63; [underlined: Change in fasting insulin (μIU/L) over 12mo], Mean (SE); Water: −0.0 (6.4), P=0.99; LNCSB: −5.4 (6.3), P=0.39; SSB: 7.5 (7.1), P=0.26; Between groups: P=0.37; [underlined: Change in insulin sensitivity % over 12mo], Mean (SE); Water: −0.6 (6.3), P=0.93; LNCSB: 4.9 (6.9), P=0.46; SSB: −7.5 (6.1), P=0.22; Between groups: P=0.38 | Model adjustments:; - TEI: no; Limitations:; - Methods for randomization and concealment NR; - Not sufficiently powered; - Trial registry did not include data analysis plan; Funding:; NHLBI; NIDDK; National Center for Research Resources; Harvard Catalyst Clinical and Translational Science Center; New Balance Foundation
Engel, 2018 ^15^; RCT-Parallel, Denmark; Baseline N=73, Analytic N=58 (Attrition: 21%); Study objective: To investigate the long-term effects of semi-skimmed milk on insulin sensitivity and further to compare milk with sugar-sweetened soft drinks and non-caloric soft drinks; Participant characteristics at baseline: adults with overweight and obesity; - Age (mean and/or range): ~39y; 20-50y; - Female: 64%; - Race and/or ethnicity: NR; - Socioeconomic position: NR; - Anthropometry: BMI ~32 kg/m^2^; - Physical activity: NR; - Family history of diabetes: NR; - Smoking: All nonsmokers; - Alcohol intake: ~8 g/d (NS difference between groups); - TEI: ~2450 kcal/d; - Beverage intake at baseline: Mean SSB intake: 184 mL/d; Excluded from study or analysis: <20 or >50y; BMI <26 or >40 kg/m^2^; diabetes; blood pressure >160/100 mmHg; medication affecting either blood lipids, blood glucose or body weight; smoking; pregnancy or breastfeeding; allergies to milk or suffering from phenylketonuria; excessive physical activity (>10 hr/wk) | Intervention: Sugar-sweetened soft drinks (SSSD, n=14): sucrose-sweetened regular cola (Coca Cola); - Serving Size: 1 L/d; Comparator: Water (n=16): still mineral water (Aqua d’or; 1 L/d); Artificially-sweetened non-caloric soft drinks (NCSD, n=15): aspartame-sweetened diet cola (Coca Colas); Duration: 26wk; Compliance: Empty bottles or cartons every 3-4wk; 7-d dietary records at baseline, 3mo, 6mo; data NR; Outcome assessment methods and timing:; - Fasting blood samples were collected and 120-min OGTT was conducted to assess various measures of insulin sensitivity (Matsuda Index, fasting, and AUC glucose, insulin and homeostasis model assessment values).; - Baseline, 6mo follow-up | [underlined: Fasting glucose (mmol/L)], Mean (SE); Within group: Baseline, 6mo; Water: 5.26 (0.54), 5.35 (0.15); NCSD: 5.52 (0.47), 5.49 (0.15); SSSD: 5.48 (0.52), 5.62 (0.18); Between groups, change over 6mo: P=NS; [underlined: Fasting insulin (pmol/L)], Mean (SE); Within group: Baseline, 6mo; Water: 68.09 (54.67), 93.19 (24.94); NCSD: 75.35 (30.64), 74.73 (10.13); SSSD: 55.32 (22.88), 61.10 (6.77); Between groups, change over 6mo: P=NS; [underlined: AUC OGTT glucose (mmol/L)], Mean (SE); Within group: Baseline, 6mo; Water: 829 (204), 812 (62); NCSD: 864 (214), 876 (61); SSSD: 889 (228), 883 (60); Between groups, change over 6mo: P=NS; [underlined: AUC OGTT insulin (pmol/L)], Mean (SE); Within group: Baseline, 6mo; Water: 25,784 (10,735), 17,786 (2726); NCSD: 32,396 (12,305), 22,766 (3090); SSSD: 24,834 (8808), 24,364 (4889); Between groups, change over 6mo: P=NS; [underlined: Matsuda Index], Mean (SE); Within group: Baseline, 6mo; Water: 7.98 (4.07), 8.38 (1.27); NCSD: 6.01 (3.55), 6.14 (0.84); SSSD: 8.08 (4.56), 6.58 (0.74); Between groups, change over 6mo: P=NS; [underlined: HOMA-IR], Mean (SE); Within group: Baseline, 6mo; Water: 1.29 (1.04), 1.71 (0.44); NCSD: 1.44 (0.58), 1.42 (0.19); SSSD: 1.06 (0.44), 1.17 (0.13); Between groups, change over 6mo: P=NS | Model adjustments:; - TEI: yes (NS difference between groups); Limitations:; - Methods for randomization and concealment NR; - No evidence whether the result was biased due to missing data; - No power calculation; - Trial registry did not include data analysis plan; Funding:; Danish Council for Strategic Research; The Food Study Group/Danish Ministry of Food, Agriculture and Fisheries; Novo Nordic Foundation; Clinical Institute at Aarhus University, Denmark; Danish Dairy Company, Arla Foods; [underlined: HOMA-IR AUC], Mean (SE); Within group: Baseline, 6mo; Water: 3.08 (3.26), 3.08 (0.82); NCSD: 2.58 (1.50), 2.58 (0.39); SSSD: 2.12 (0.89), 2.12 (0.25); Between groups, change over 6mo: P=NS
Hernandez-Cordero, 2014 ^21^; RCT-Parallel, Mexico; Baseline N=240, Analytic N=240 (Attrition: 0%); Study objective: To determine if replacing SSBs with water affects plasma triglycerides TGs (primary outcome), weight, and other cardiometabolic factors; Participant characteristics at baseline: adult women with overweight and obesity; - Age (mean and/or range): 33 (6.7)y; 18-45y; - Female: 100%; - Race and/or ethnicity: 100% Hispanic; - Socioeconomic position: 45% completed middle and high school; Socioeconomic level index (composite score including age, years of education, and housing condition): WEP: 0.11(1.34), EP: −0.14(1.33), P>0.05; - Anthropometry: BMI 31.2 (3.7) kg/m^2^; 46% with overweight; 54% with obesity; - Physical activity: 1.455 (0.004) METs/d; - Family history of diabetes: NR; - Smoking: 31% current; - Alcohol intake: NR; - TEI: ~2035 kcal/d; - Beverage intake at baseline: All with SSB intake ≥250 cal/d (inclusion criteria) ~1,111 mL/d, ~408 kcal/d, ~21% of TEI; Excluded from study or analysis: <18 or >45y; BMI <25 or ≥39 kg/m^2^; SSB intake <250 kcal/d; >5% weight loss in past 6mo; current weight-reducing diet; pregnancy in past 6mo; medical condition that affects metabolic function; history of MI or heart surgery; medication affecting metabolism; recent psychiatric hospitalization; muscle-increasing regime or anabolic use; excessive alcohol (≥21 drinks/wk) | Intervention: Participants with habitually high SSB intake (≥250 cal/d) were randomized to 1 of 2 groups: water+education (WEP) or education only (EP).; SSB (EP, n=120): habitual SSB intake ≥250 cal/d plus monthly face-to-face nutrition counseling with a dietitian and a psychologist where they identified a healthy diet goal for the next month; - Serving Size: NR; Comparator: Water (WEP, n=120): received bottled water (2-3 L/d) with monthly face-to-face nutrition counseling with a dietitian and a psychologist, including individualized and group meetings targeted to the rationale and strategies to increase water intake, reduce SSB intake, and substitute water for SSBs; Duration: 9mo (39wk); Compliance: Attendance (Mean (SD)): WEP: 7.3(2.4) sessions; EP: 6.4(2.4) sessions; P=0.01; SSB decreased in both groups but more in WEP; Outcome assessment methods and timing:; - Fasting blood samples were collected and the proportion of HbA1C was determined by an immunocolorimetric method in whole blood; - Baseline, 3, 6, and 9mo follow-up for fasting blood glucose; baseline and 9mo for HbA1C | [underlined: Fasting plasma glucose (mg/dL)], Mean (SE); Within group: Baseline, 3mo, 6mo, 9mo; Water (WEP): 90.2 (0.4), 90.0 (0.3), 90.5 (0.3), 90.7 (0.4); SSB (EP): 90.2 (0.3), 90.3 (0.3), 90.5 (0.4), 91.1 (0.3); Between groups: Change over 3mo; Water (WEP): 0.04 (1.5); SSB (EP): 0.2 (1.4); P=0.90; Change over 6mo; Water (WEP): 0.60 (1.90); SSB (EP): 0.90 (2.20); P=0.90; Change over 9mo; Water (WEP): 1.20 (1.70); SSB (EP): 1.70 (2.80); P=0.90; [underlined: HbA1C (%)], Mean (SE); Within group: Baseline, 9mo; Water (WEP): 5.80 (0.01), 5.82 (0.01); SSB (EP): 5.80 (0.01), 5.80 (0.01); P(treatment)=0.20; P(time)=0.30; Between groups: Change over 9mo; Water (WEP): −0.03 (0.03); SSB (EP): 0.02 (0.03); P=0.30 | Model adjustments:; - TEI: no; Limitations:; - The EP group was not required to maintain SSB intake; Funding:; Danone Research Center
Kendig, 2023 ^27^; RCT-Parallel, Australia; Baseline N=118, Analytic N=80 (Attrition: 32%); Study objective: To assess the effects of a 12-week intervention in which young healthy adults who regularly consumed SSBs were instructed to replace SSB intake with artificially-sweetened beverages, water, or to continue SSB intake.; Participant characteristics at baseline: young adults that habitually consume SSB; - Age (mean and/or range): 22.9 (3.9)y; 18-35y; - Female: 40%; - Race and/or ethnicity: NR; - Socioeconomic position: NR; - Anthropometry: BMI 23.2 (3.6) kg/m^2^; - Physical activity: NR; - Family history of diabetes: NR; - Smoking: NR; - Alcohol intake: NR; - TEI: NR; - Beverage intake at baseline: All drank >2 L/wk of SSB; Excluded from study or analysis: <18 or >35y; BMI <17.5 or >30 kg/m^2^; regularly consumed less than 2 L/wk of SSB; participants with average weekly SSB intake >1.5 times their group’s IQR | Intervention: SSB (n=27): commercially available; - Serving Size: 4.5 L/wk (as 12 × 375mL cans and ≤3 cans/d); Comparator: Water (n=25): 4.5 L/wk as 12 × 375mL cans; Artificially-sweetened beverages (n=28): 4.5 L/wk as 12 × 375mL cans and ≤3 cans/d; Duration: 12wk; Compliance: questionnaire on weekly drink adherence and weekly SSB intake; Outcome assessment methods and timing:; - Fasting blood samples were collected and 60-min OGTT was conducted.; - Baseline (test 1), 12wk (test 3) | [underlined: Change in OGTT blood glucose (mM) over 12wk]; Water vs Artificially-sweetened beverages vs SSB: data NR (figure only), P=NS | Model adjustments:; - TEI: no; Limitations:; - Methods for randomization and concealment NR; - Concerns with deviations from intended intervention; - High attrition rate with no information on non-completers; - Not sufficiently powered; - Trial registry did not include data analysis plan; Funding:; Australian Research Council Discovery Project
Tate, 2012 ^44^; RCT-Parallel, CHOICE (Choose Healthy Options Consciously Everyday), U.S.; Baseline N=318, Analytic N=313 (Attrition: 2%); Study objective: To compare the replacement of caloric beverages with water or diet beverages as a method of weight loss over 6mo in adults and attention controls; Participant characteristics at baseline: adults with overweight and obesity; - Age (mean and/or range): 42 (10.7)y; 18-65y; - Female: 84%; - Race and/or ethnicity: 40% White; 54% Black; 6% Other; - Socioeconomic position: 52% college graduate or beyond; 39% some college; 9% high school or less; 54% married or living with partner; - Anthropometry: BMI 36.3 (5.9) kg/m^2^; - Physical activity: NR; - Family history of diabetes: NR; - Smoking: 8% current; 25% former; - Alcohol intake: NR; - TEI: ~2170 kcal/d; - Beverage intake at baseline: All consumed ≥280 kcal/d of caloric beverages; ~100-200 g/d; Excluded from study or analysis: <18 or 65y; BMI <25 or >49.9 kg/m^2^; consumed <280 kcal/d of caloric beverages; recent weight loss of >5%; participation in other weight-loss or physicalactivity research; lactation; recent or planned pregnancy; thyroid medication use; diabetes mellitus treated with oral medication or insulin; cancer in prior 5y; history of myocardial infarction or heart surgery; current psychiatric treatment; psychiatric hospitalization in past year; alcohol dependence; plans to move or unable to attend monthly group meetings; inadequate means to transport beverages; self-report of heart problems, frequent chest pains, or faintness or dizziness | Intervention: Participants with high habitual SSB intake (≥280kcal/d) assigned to 1 of 3 groups: attention control (maintain SSB intake), water, or diet beverages (LNCSB).; “Attention Control” (AC, n=105): equal treatment contact time and attention involving monthly group sessions and weigh-ins, weekly monitoring, general weight-loss information (e.g., product labels, portion control, physical activity). Participants were not provided with beverages, given weight-loss or physical activity goals, or encouraged to change beverage intake.; - Serving Size: 355-500 mL (12-16oz); Comparator: Diet beverages (n=105): encouraged to replace ≥2 svg/d (≥200 kcal) of caloric beverages with diet beverages (any combination of noncaloric sweetened beverages: carbonated, noncarbonated, noncaffeinated, and caffeinated beverages), which were provided at monthly group meetings; Water (n=108): encouraged to replace ≥2 svg/d (≥200 kcal) of caloric beverages with water (any combination of bottled still and non-sweetened sparkling water), which were provided at monthly group meetings; Duration: 26wk; Compliance: Monthly group counseling to promote adherence; DB and Water groups attended significantly more group sessions than AC group. Two unannounced 24-h dietary recalls were administered via telephone (1 weekday and 1 weekend day) at baseline, 3mo, and 6mo.; Outcome assessment methods and timing:; - Fasting blood samples were collected; - Baseline, 3mo and 6mo follow-up | [underlined: Fasting blood glucose (mg/dL)], Mean (95% CI); Within group: Baseline, 3mo, 6mo; LNCSB: 91.7 (89.3, 94.1); 90.2 (87.7, 92.7); 89.7 (87.6, 91.9), P=0.0978; Water: 93.1 (88.9, 97.2); 90.1 (85.7, 94.6); 89.9 (87.4, 92.3), P=0.0027; Attention Control: 88.6 (86.6, 90.6); 87.5 (85.1, 89.9); 89.2 (87.2, 91.1), P=0.0058; Between groups: Change over 6mo; Water: −3.21 (−3.89, −2.53); LNCSB: −1.92 (−2.38, −1.46); Attention Control: 0.59 (0.35, 0.83); Water vs Attention Control: P=0.019; LNCSB vs Attention Control: P=0.1471 | Model adjustments:; - TEI: no; Limitations:; - Amount of carbonated and/or caffeinated versions of beverages was not taken into account; - Trial registry did not include data analysis plan; Funding:; Nestlé Waters USA

a Abbreviations: ASB: artificial sweetened beverage(s); BMI: body mass index; d: day(s); dL: deciliter; HbA1c: hemoglobin A1C; HOMA-IR: homeostatic model assessment for insulin resistance; hr: hour; IAUC: incremental area under the curve; IQR: interquartile range; kcal: kilocalorie(s); kg: kilogram(s); L: liter(s); LNCSB: low- and no-calorie sweetened beverage(s); m: meter(s); mg: milligram(s); min: minute(s); mL: milliliter(s); mM: millimole(s); NA: not applicable; NIDDK: National Institute of Diabetes and Digestive and Kidney Diseases; nmol: nanomole; NR: not reported; NS: not significant; OGTT: oral glucose tolerance test; oz: ounce(s); RCT: randomized controlled trial; REF: reference group; SD: standard deviation; SE: standard error; SEM: standard error of the mean; SSB: sugar-sweetened beverage(s); svg: serving(s); TEI: total energy intake; μmol: micromole; wk: week(s); y: year(s)

Table 11 Observational studies examining the relationship between sugar-sweetened beverage consumption in adults and older adults and risk of type 2 diabetes^a^

Study and Participant Characteristics | Exposure, Comparator, and Outcome(s) | Results | Methodological Considerations
Bazzano, 2008 ^6^; PCS, NHS (Nurses’ Health Study), U.S.; Analytic N=71,346; Study objective: To examine the association between fruit, vegetable, and fruit juice intake and development of T2D; Participant characteristics at baseline: women; - Age (mean and/or range): 50 (7)y; 38-63y; - Female: 100%; - Race and/or ethnicity: Primarily Caucasian; - Socioeconomic position: All nurses; - Anthropometry: BMI 23 (7) kg/m^2^; - Physical activity: 2 (2) hr/wk; - Family history of diabetes: 25%; - Smoking: 24% current; - Alcohol intake: 7 (11) g/d; - TEI: 1457-2061 kcal/d; - Beverage intake at baseline: NR; Excluded from study or analysis: baseline diabetes; cancer or cardiovascular disease; missing data; loss to follow-up; energy intake <600 or >3500 kcal/d | Exposure: 3 separate beverage categories: Sugar-sweetened cola; “Other carbonated beverages” (details NR, likely combined sugar- and artificially-sweetened beverages); Fruit punch; - Serving Size: NR; Comparator: continuous intake (svg/d); Assessment methods and timing:; - FFQ assessing usual intake during previous year.; - 1984, 1986, 1990, 1994, 1998 (cumulative average of median values from all available questionnaires up to the start of each 2y follow-up period); Outcome assessment methods and timing:; - Self-reported via biennial questionnaire; verified with supplementary questionnaire specific to T2D; - 18y | [underlined: T2D by cumulative average of median intake], HR (95% CI); Per 1 svg/d increase:; Sugar-sweetened cola: 1.08 (1.04, 1.12); Carbonated beverages: 1.04 (1.00, 1.09); Fruit punch: 1.10 (1.06, 1.15) | Model adjustments:; - TEI: yes; - Key confounders: sex, age, anthropometry, physical activity, family history of diabetes, smoking, alcohol intake; - Other: postmenopausal hormone use; consumption of whole grains, nuts, processed meats, coffee, and potatoes; Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position; - Exposure not well defined; - No evidence whether the result was biased due to missing data; - No preregistered data analysis plan; Funding:; NIH
Bhupathiraju, 2013 ^7^; PCS, NHS (Nurses’ Health Study) and HPFS (Health Professionals Follow-up Study), U.S.; Analytic N=74,749 (NHS); 39,059 (HPFS); Study objective: To prospectively examine the association of caffeinated compared with caffeine-free beverages, including coffee, tea, SSB, and carbonated artificially sweetened beverages, with T2D risk; Participant characteristics at baseline: nurses and health professionals; - Age (mean and/or range): ~50y, 38-63y (NHS); ~53y, 40-75y (HPFS); - Female: 100% (NHS), 0% (HPFS); - Race and/or ethnicity: Primarily Caucasian; - Socioeconomic position: Mainly educated health professionals; - Anthropometry: BMI ~25 kg/m^2^ in both NHS and HPFS; - Physical activity: METs/wk, ~14 (NHS); ~21 (HPFS); - Family history of diabetes: 28% NHS; 20% HPFS; - Smoking: current, 25% NHS; 9% HPFS; - Alcohol intake: ~7 g/d in NHS; ~11 g/d in HPFS; - TEI: ~1800 kcal/d (NHS); ~2000 kcal/d (HPFS); - Beverage intake at baseline: ~0.3 svg/d SSB in both NHS and HPFS; Excluded from study or analysis: baseline diabetes; cancer or cardiovascular disease; women who left ≥10 items blank on FFQ or energy intakes <500 or >3500 kcal/d; men who left ≥70 items blank on the FFQ or energy intake <800 or >4200 kcal/d | Exposure: SSB (colas and carbonated soft drinks, examined separately as caffeinated and caffeine-free); - Serving Size: ~355 mL (“one standard glass, can, or bottle”); Comparator: continuous intake (per 1 svg/d); categorical intake (<1/mo, 1-4/mo, 2-6/wk, ≥1/d); Assessment methods and timing:; - FFQ assessing usual intake during previous year.; - Baseline (1984 in NHS, 1986 in HPFS), and every 4y for 22-24y follow-up (until 2008 in NHS and 2008 in HPFS) - cumulative average of intake; Outcome assessment methods and timing:; - Self-reported via biennial questionnaire; verified with supplementary questionnaire specific to T2D; - Up to 2008, maximum 22y (HPFS) and 24y (NHS) | [underlined: T2D by cumulative average intake], RR (95% CI); NHS; Caffeinated SSB; <1/mo (ref); 1-4/mo: 1.08 (1.01, 1.15); 2-6/wk: 1.19 (1.09, 1.28); ≥1/d: 1.29 (1.14, 1.47); P-trend<0.0001; Per-serving increment: 1.13 (1.06, 1.20); Caffeine-free SSB; <1/mo (ref); 1-4/mo: 1.01 (0.95, 1.07); 2-6/wk: 1.02 (0.95, 1.11); ≥1/d: 1.20 (1.01, 1.42); P-trend=0.05; Per-serving increment: 1.11 (1.00, 1.23); HPFS; Caffeinated SSB; <1/mo (ref); 1-4/mo: 1.05 (0.95, 1.16); 2-6/wk: 1.19 (1.06, 1.34); ≥1/d: 1.33 (1.10, 1.60); P-trend<0.001; Per-serving increment: 1.16 (1.06, 1.27); Caffeine-free SSB; <1/mo (ref); 1-4/mo: 1.02 (0.93, 1.13); 2-6/wk: 1.14 (1.01, 1.29); ≥1/d: 1.37 (1.08, 1.74); P-trend=0.002; Per-serving increment: 1.23 (1.06, 1.43); No significant interaction between beverage intake and BMI, physical activity, or smoking (data not shown). | Model adjustments:; - TEI: yes; - Key confounders: sex, age, anthropometry, physical activity, family history of diabetes, smoking, alcohol intake; - Other: postmenopausal hormone use (NHS), alternative HEI, and consumption of other beverages other than the main exposure, depending on model, presence of hypertension, hypercholesterolemia, adherence to low-calorie diet; Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position; - No evidence whether the result was biased due to missing data; - No preregistered data analysis plan; Funding:; NIH
Canhada, 2023 ^9^; PCS, ELSA-Brasil, Brazil; Analytic N=10,202; Study objective: To investigate the association of ultra-processed food (UPF) consumption and specific subgroups with incident T2D in Brazilian adults.; Participant characteristics at baseline: Brazilian adults; - Age (mean and/or range): Median 50y (IQR: 44-57); 35-74y; - Female: 57%; - Race and/or ethnicity: 55% White; 15% Black; 2% Asian; 1% Indigenous; 27% Brown; - Socioeconomic position: 58% college/university degree, 33% secondary education, 9% elementary education or less; Median 1452 Brazilian reais (IQR: 726-2282); - Anthropometry: BMI 25.9 (23.4-28.9) kg/m^2^; - Physical activity: Median: 264 METs/wk (IRQ: 0-960); - Family history of diabetes: 36%; - Smoking: 12% current; 28% former; 60% never; - Alcohol intake: Median 0 g/wk (IQR: 0-65.6); - TEI: Median 2450 kcal/d (IQR: 1946-3120); - Beverage intake at baseline: NR; Excluded from study or analysis: baseline diabetes; missing data or loss to follow-up; implausible food intake; bariatric surgery | Exposure: Sweetened beverages as subgroup of UPF (diet soda, soda, industrialized juice with sugar, industrialized juice without sugar, industrialized juice with sweetener, artificial juice with sugar, artificial juice without sugar, artificial juice with sweetener); - Serving Size: NR; Comparator: continuous intake (per 50 g/d and SD/d); Assessment methods and timing:; - FFQ assessing usual intake during previous year.; - Baseline; Outcome assessment methods and timing:; - Self-report of physician-diagnosed T2D or current use of diabetes medication, or biomarkers (FPG >126 mg/dl, 2hr post-load glucose >200 mg/dL, or HbA1C 6.5%); - 8.2 (0.7)y | [underlined: T2D by baseline intake], RR (95% CI); By 50 g/d increase: 1.03 (1.02, 1.04); By SD (230 mL/d) increase: 1.14 (1.10, 1.18) | Model adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position (income; school achievement), physical activity, family history of diabetes, smoking, alcohol intake; - Other: none; Limitations:; - Did not account for key confounders: anthropometry; - Exposure subject to measurement error (combined SSB and LNCSB) and only assessed at baseline; - No evidence whether the result was biased due to missing data; - No preregistered data analysis plan; Funding:; Brazilian Ministry of Health; Ministry of Science, Technology, and Innovation; National Council for Scientific and Technological Development
Chen, 2023 ^10^; PCS, NHS (Nurses’ Health Study), NHS-II, HPFS (Health Professionals Follow-Up Study), U.S.; Analytic N=198,636 (71,871 in NHS; 87,918 in NHS-II; 38,847 in HPFS); Study objective: To examine the relationship between ultra-processed food intake and T2D risk among 3 large U.S. cohorts; Participant characteristics at baseline: nurses and health professionals; - Age (mean and/or range): ~50y, 38-63y (NHS); ~36y, 27-44y (NHS-II); ~52y, 40-75y (HPFS); - Female: 80%; - Race and/or ethnicity: Primarily Caucasian; - Socioeconomic position: Mainly educated health professionals; - Anthropometry: BMI ~26 kg/m^2^; - Physical activity: MET-hr/wk, ~26 (NHS); ~18 (NHS-II); ~34 (HPFS); - Family history of diabetes: 27% NHS; 33% NHS-II; 14% HPFS; - Smoking: current, 10% NHS; 9% NHS-II; 6% HPFS; - Alcohol intake: ~5.5 g/d (NHS); ~3.5 g/d (NHS-II); ~10.5 g/d (HPFS); - TEI: ~1800 kcal/d (NHS and NHS-II); ~2000 kcal/d (HPFS); - Beverage intake at baseline: 0.3 (0.5) svg/d of SSB; Excluded from study or analysis: baseline diabetes; cancer or cardiovascular disease; missing data; loss to follow-up; energy intake <500 or >3500 kcal/d for women, <800 or >4200 kcal/d for men | Exposure: SSB (7-up; Coke or Pepsi with caffeine & sugar; Coke or Pepsi without CI) caffeine but with sugar; Hawaiian punch Per 1 svg/d increase: 1.15 (1.12, 1.17) with sugar; Other carbonated beverage; Dairy coffee drinks); - Serving Size: NR; Comparator: continuous intake (per 1 svg/d increase); Assessment methods and timing:; - FFQ assessing usual intake during previous year.; - Baseline (1984 in NHS, 1986 in HPFS, 1991 in NHS-II), and every 4y until 2016 in NHS and HPFS and until 2017 in NHS-II; Outcome assessment methods and timing:; - Self-reported via biennial questionnaire; verified with supplementary questionnaire specific to T2D; - Up to 2016 in NHS and HPFS, and up to 2017 in NHS-II | [underlined: T2D by cumulative average intake], HR (95% CI); Per 1 svg/d increase: 1.15 (1.12, 1.17) | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position (neighborhood income), anthropometry, physical activity, family history of diabetes, smoking, alcohol intake; - Other: physical examination; menopausal status (NHS-II); postmenopausal hormone use (NHS and NHS-II); oral contraceptive use (NHS-II); history of hypercholesterolemia and hypertension; other ultra-processed food subgroups; Limitations:; - No evidence whether the result was biased due to missing data; - No preregistered data analysis plan; Funding:; NIH
Cho, 2023 ^11^; PCS, KoGES (Korean Genome and Epidemiology Study), South Korea; Analytic N=7,438; Study objective: To examine the associations of ultra-processed food intake (combined, as well as individual ultra-processed food items) with the risk of T2D; Participant characteristics at baseline: Korean middle-aged adults; - Age (mean and/or range): 51.7y; 40-69y; - Female: 47%; - Race and/or ethnicity: All Asian; - Socioeconomic position: 14% college or higher, 31% high school, 54% lower than high school; 33% lowest household income (compared to mid to low, mid to high, and highest); 48% physical labor occupation, 28% homemakers; - Anthropometry: 41% with overweight; - Physical activity: 66% high, 2% low, 31% none; - Family history of diabetes: NR; - Smoking: 25% current; 15% former; 59% never; - Alcohol intake: 52% nondrinker, 30% low intake, 16% high intake; - TEI: 1723-2109 kcal/d; - Beverage intake at baseline: NR; Excluded from study or analysis: baseline diabetes; missing data or loss to follow-up; energy intake <800 or >4000 kcal/d for men, <500 or >3500 kcal/d for women | Exposure: SSB, including carbonated sugar-sweetened beverages (coke, sprite) and other sugar-sweetened beverages rice punch, yuja citron tea, etc.); - Serving Size: NR; Comparator: continuous intake (per 1% increase in weight ratio); Assessment methods and timing:; - FFQ assessing usual intake during previous year.; - Baseline; Outcome assessment methods and timing:; - Self-report; confirmed through FBG and HbA1C measured at health examinations; - 12.9y; Median: 15y | [underlined: T2D by baseline intake], HR (95% CI); Per 1% increase in weight ratio; Total SSB: 1.01 (0.99, 1.03); Carbonated SSB: 1.02 (1.00, 1.04); Other SSB: 0.99 (0.95, 1.04) | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position (educational attainment; household income; occupation; marital status), physical activity, smoking, alcohol intake; - Other: history of coronary artery disease, stroke, hypertension, or dyslipidemia; ultraprocessed food items; survey district (Ansan, Ansung); Limitations:; - Did not account for key confounders: anthropometry, family history of diabetes; - Exposure only assessed at baseline; - No evidence whether the result was biased due to missing data; - No preregistered data analysis plan; Funding:; National Research Foundation of Korea
de Koning, 2011 ^12^; PCS, HPFS (Health Professionals Follow-up Study), U.S.; Analytic N=41,109; Study objective: To examine the associations of SSB and ASB with incident T2D; Participant characteristics at baseline: male health professionals; - Age (mean and/or range): 51y; 40-75y; - Female: 0%; - Race and/or ethnicity: Primarily Caucasian; - Socioeconomic position: All health professionals; - Anthropometry: BMI ~25.5 (3.2) kg/m^2^; - Physical activity: ~21 METs/wk; - Family history of diabetes: 12%; - Smoking: 9% current; - Alcohol intake: ~11 g/d; - TEI: ~1950 kcal/d; - Beverage intake at baseline: 0.36 (0.61) svg/d of total SSB; Excluded from study or analysis: baseline diabetes; <40 or >75y at recruitment, T1D, cardiovascular disease (heart attack, stroke, angina, coronary artery bypass graft), cancer (except melanoma skin cancer), energy intake <800 or >4299 kcal/d | Exposure: SSB (caffeinated colas, caffeine-free colas, other carbonated sugar-sweetened beverages, and noncarbonated sugar-sweetened beverages such as fruit punches, lemonades, or other fruit drinks); - Serving Size: 1 svg = “one standard glass, can, or bottle”; Comparator: continuous intake (per 1 svg/d); categorical intake (quartiles); - Quartile 1: never; - Quartile 2: 2/mo; - Quartile 3: 1-4/wk; - Quartile 4: 4.5/wk to 7.5/d; Assessment methods and timing:; - FFQ assessing usual intake during previous year.; - Baseline, and every 4y for 20y; Outcome assessment methods and timing:; - Self-reported via biennial questionnaire; verified with supplementary questionnaire specific to T2D; - 20y | [underlined: T2D by cumulative average intake of total SSB], HR (95% CI); Q1: REF; Q2: 1.09 (0.97, 1.22); Q3: 1.07 (0.95, 1.20); Q4: 1.24 (1.09, 1.40); P-trend<0.01; By 1 svg/d increase of total SSB: 1.16 (1.08, 1.25), P<0.01; By 1 svg/d increase of caffeinated and noncaffeinated colas: 1.20 (1.09, 1.32), P<0.01; By 1 svg/d increase of carbonated noncolas: 1.35 (1.08, 1.69), P<0.01; By 1 svg/d increase of fruit punches, lemonades, other noncarbonated fruit drinks: 1.05 (0.89, 1.25), P=0.65; By baseline intake of total SSB; Q1: REF; Q4: 1.19 (1.07, 1.33); P-trend<0.01; No significant interactions between beverage intake and age, alcohol, physical activity, or family history (data not shown). | Model adjustments:; - TEI: yes; - Key confounders: sex, age, anthropometry, physical activity, family history of diabetes, smoking, alcohol intake; - Other: multivitamin use, high triglycerides, high blood pressure, use of diuretics, previous weight change and low-calorie diet, alternative HEI; Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position; - No evidence whether the result was biased due to missing data; - No preregistered data analysis plan; Funding:; NIH; Canadian Institutes of Health Research; Canadian Diabetes Association
Drouin-Chartier, 2019 ^13^; PCS, NHS (Nurses’ Health Study), NHS-II, HPFS (Health Professionals Follow-Up Study), U.S.; Analytic N=192,352 (76,531 in NHS; 81,597 in NHS-II; 34,224 in HPFS); Study objective: To evaluate the associations of long-term changes in consumption of SSB and ASB with subsequent risk of T2D; Participant characteristics at baseline: nurses and health professionals; - Age (mean and/or range): ~58y, 52-77y (NHS); ~41y, 37-54y (NHS-II); ~57y, 54-89y (HPFS); - Female: 82%; - Race and/or ethnicity: Primarily Caucasian; - Socioeconomic position: Mainly educated health professionals; - Anthropometry: BMI ~25 kg/m^2^; - Physical activity: MET-hr/wk, ~15 (NHS); ~24 (NHS-II); ~20 (HPFS); - Family history of diabetes: 28% NHS; 34% NHS-II; 26% HPFS; - Smoking: current, 19% NHS; 11% NHS-II; 8% HPFS; - Alcohol intake: NR; - TEI: ~1700 kcal/d (NHS and NHS-II); ~2000 kcal/d (HPFS); - Beverage intake at baseline: ~0.4 svg/d (NHS); ~0.7 svg/d (NHS-II); ~0.6 svg/d (HPFS); Excluded from study or analysis: baseline diabetes; cancer or cardiovascular disease; missing data; loss to follow-up; energy intake <500 or >3500 kcal/d for women, <800 or >4200 kcal/d for men | Exposure: SSB (carbonated and noncarbonated beverages with sugar, such as soft drink, punch, lemonade, fruit drink, or sugared ice tea); - Serving Size: 8oz (converted for analysis from one 12-oz glass, bottle, or can); Comparator: categorical intake (change in beverage intake); - Decrease in consumption >0.50 svg/d; - Decrease in consumption >0.07-0.50 svg/d; - No change or relatively stable consumption (±0.07 svg/d); - Increase in consumption >0.07-0.50 svg/d; - Increase in consumption >0.50 svg/d; Assessment methods and timing:; - FFQ assessing usual intake during previous year.; - Baseline (1990 in NHS and HPFS, 1995 in NHS-II), and every 4y for up to 26y follow-up (analyzed 4y change in beverage intake on risk of T2D in the subsequent 4y period); Outcome assessment methods and timing:; - Self-reported via biennial questionnaire; verified with supplementary questionnaire specific to T2D; - Up to 2012 in NHS and HPFS, and up to 2013 in NHS-II | [underlined: T2D by 4y change in intake], HR (95% CI); Pooled (all cohorts); Decrease >0.50 svg/d: 1.01 (0.94, 1.09); Decrease >0.07-0.50 svg/d: 1.02 (0.95, 1.09); No change: REF; Increase >0.07-0.50 svg/d: 1.03 (0.97, 1.09); Increase >0.50 svg/d: 1.09 (1.03, 1.17); P-trend=0.006; Stratified analysis of pooled results also provided by initial AHEI index, obesity, and physical activity – no significant interactions; NHS; Decrease >0.50 svg/d: 1.02 (0.92, 1.14); Decrease >0.07-0.50 svg/d: 1.03 (0.94, 1.13); No change: REF; Increase >0.07-0.50 svg/d: 1.04 (0.96, 1.12); Increase >0.50 svg/d: 1.10 (1.00, 1.20); P-trend=0.12; NHS-II; Decrease >0.50 svg/d: 0.92 (0.81, 1.06); Decrease >0.07-0.50 svg/d: 0.99 (0.87, 1.11); No change: REF; Increase >0.07-0.50 svg/d: 1.04 (0.93, 1.16); Increase >0.50 svg/d: 1.13 (1.00, 1.27); P-trend=0.001; HPFS; Decrease >0.50 svg/d: 1.15 (0.97, 1.37); Decrease >0.07-0.50 svg/d: 1.03 (0.90, 1.19); No change: REF; Increase >0.07-0.50 svg/d: 0.99 (0.88, 1.12); Increase >0.50 svg/d: 1.03 (0.89, 1.20); P-trend=0.29 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, anthropometry, physical activity, family history of diabetes, smoking, alcohol intake; - Other: physical examination; menopausal status; postmenopausal hormone use; oral contraceptive use; AHEI score; intake of other beverages; Limitations:; - Did not account for key confounders: socioeconomic position; - No evidence whether the result was biased due to missing data; - No preregistered data analysis plan; Funding:; NIH
Ericson, 2018 ^16^; PCS, Malmö Diet and Cancer, Sweden; Analytic N=25,069; Study objective: To examine the interaction between a genetic risk score for T2D and a diet risk score of processed meat, SSB, whole grain, and coffee; Participant characteristics at baseline: middle-aged and older adults; - Age (mean and/or range): 58 (7)y; 45-74y; - Female: 61%; - Race and/or ethnicity: NR; - Socioeconomic position: 32% education >10y; - Anthropometry: BMI 25 (4) kg/m^2^; - Physical activity: 20% high leisure time physical activity; - Family history of diabetes: NR; - Smoking: 62% ever; - Alcohol intake: 11 (12) g/d; - TEI: NR; - Beverage intake at baseline: 33% zero-consumers of SSB; mean intake ~77 g/d; Excluded from study or analysis: baseline diabetes; missing data; loss to follow-up | Exposure: SSB (beverages sweetened with energy-containing sweeteners; mainly sucrose); - Serving Size: NR; Comparator: categorical intake (tertiles); - Tertile 1: zero-consumers of SSB; - Tertile 2: below median of SSB consumers; - Tertile 3: above median of SSB consumers; Assessment methods and timing:; - Validated, modified diet history (7d food diary, FFQ assessing usual intake during previous year, and 45- or 60-min interview); - Baseline; Outcome assessment methods and timing:; - National registries (90% of cases) or follow-up examinations (10% of cases); - Mean follow-up time: 17 (5.6)y; Range: 0-24y | [underlined: T2D by baseline intake], HR (95% CI); All; Tertile 1: REF; Tertile 2: 1.01 (0.93, 1.10); Tertile 3: 1.13 (1.05, 1.22); P-trend=0.003; Women; Tertile 1: REF; Tertile 2: 1.06 (0.94, 1.20); Tertile 3: 1.12 (1.01, 1.25); P-trend=0.03; Men; Tertile 1: REF; Tertile 2: 0.95 (0.84, 1.07); Tertile 3: 1.14 (1.01, 1.28); P-trend=0.06 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, socioeconomic position (education), anthropometry, physical activity, smoking, alcohol intake; - Other: diet assessment method version, season of diet collection; Limitations:; - Did not account for key confounders: race and/or ethnicity, family history of diabetes; - Exposure only assessed at baseline; - No evidence whether the result was biased due to missing data; - No preregistered data analysis plan; Funding:; European Research Council; Swedish Research Council; Swedish Heart and Lung Foundation; Region Skåne; Novo Nordic Foundation; Albert Påhlsson Research Foundation
Eshak, 2013 ^17^; PCS, Japan Public Health Center-based prospective study, Japan; Analytic N=27,585; Study objective: To examine whether increased intake of soft drink and juices contribute to T2D; Participant characteristics at baseline: Japanese adults; - Age (mean and/or range): ~49y; 40-59y; - Female: 56%; - Race and/or ethnicity: All Asian; - Socioeconomic position: 50% >high school education; - Anthropometry: BMI 23 (3) kg/m2; - Physical activity: 15% practice sports ≥3 times/wk; - Family history of diabetes: 8%; - Smoking: 25% current (mean ~52% in men, ~4% in women); - Alcohol intake: ~53 g/d in men, ~29 g/d in women; - TEI: ~2200 kcal/d in men, ~1500 kcal/d in women; - Beverage intake at baseline: 59% rarely drink SSB; 24% drink SSB ≤2 times/wk; 10% drink SSB 3-4 times/wk; 6% SSB almost every day; Excluded from study or analysis: baseline diabetes; cardiovascular disease, cancer, kidney disease, chronic liver disease; missing data; energy intake <500 or >3500 kcal/d | Exposure: Soft drinks (cola, flavored juices, and non-100% fruit juices); - Serving Size: NR; Comparator: categorical intake (rarely, ≤2 times/wk, 3-4 times/wk, almost every day); Also, change in intake from baseline to 5y:; - Decreased intake at 5y; - Consistently no intake; - Consistently moderate intake (1-4 times/wk); - Increased intake at 5y; - Consistently high intake (almost every day); Assessment methods and timing:; - FFQ assessing usual intake during previous year.; - Baseline, 5y follow-up; Outcome assessment methods and timing:; - “Has a doctor ever told you that you have any of the following diseases? Diabetes (yes/no)” at baseline, 5y and 10y follow-up; - 5y and 10y follow-up | [underlined: T2D by baseline intake], OR (95% CI); 5y incidence; Men (n=13,854); Rarely: REF; ≤2 times/wk: 0.98 (0.76, 1.27); 3-4 times/wk: 0.79 (0.55, 1.13); Almost every day: 0.98 (0.64, 1.50); P-trend=0.73; Women (n=17,007); Rarely: REF; ≤2 times/wk: 1.20 (0.86, 1.67); 3-4 times/wk: 1.44 (0.90, 2.31); Almost every day: 2.10 (1.23, 3.59); P-trend=0.004; 10y incidence Men (n=12,137); Rarely: REF; ≤2 times/wk: 0.86 (0.68, 1.08); 3-4 times/wk: 0.83 (0.61, 1.12); Almost every day: 0.98 (0.68, 1.42); P-trend=0.80; Women (n=15,448); Rarely: REF; ≤2 times/wk: 1.15 (0.88, 1.51); 3-4 times/wk: 1.17 (0.78, 1.76); Almost every day: 1.79 (1.11, 2.89); P-trend=0.01; [underlined: T2D by change in SSB intake over 5y], OR (95% CI); Men; Decreased intake at 5y: 0.92 (0.69, 1.24); Consistently no intake: REF; Consistently moderate intake: 0.77 (0.55, 1.08); Increased intake at 5y: 0.90 (0.39, 1.18); Consistently high intake: 0.93 (0.64, 1.36); Women; Decreased intake at 5y: 0.87 (0.56, 1.36); Consistently no intake: REF; Consistently moderate intake: 1.17 (0.73, 1.87); Increased intake at 5y: 1.33 (1.01, 1.76); Consistently high intake: 1.76 (1.11, 2.87) | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position (education; occupation), anthropometry, physical activity, family history of diabetes, smoking, alcohol intake; - Other: history of hypertension, consumption of coffee and green tea, magnesium, calcium, vitamin D, rice, total dietary fiber; Limitations:; - No evidence whether the result was biased due to missing data; - Outcome was self-reported; - No preregistered data analysis plan; Funding:; Ministry of Health, Labor, and Welfare of Japan; Also provided results stratified by age (P=0.001), sports activity (P=0.06), education (P=0.004), occupation (P=0.003), BMI (P=0.007), and menopausal status (P=0.03).
Fagherazzi, 2013 ^18^; PCS, EPIC-E3N (Etude Epidémiologique auprès de femmes de la Mutuelle Générale de l’Education Nationale), France; Analytic N=66,118; Study objective: To evaluate the association between self-reported SSB, ASB, and 100% fruit juice consumption and T2D risk over 14y of follow-up; Participant characteristics at baseline: French women; - Age (mean and/or range): 52.6 (6.6)y; - Female: 100%; - Race and/or ethnicity: NR; - Socioeconomic position: 86% graduate/postgraduate education; 14% undergraduate education; - Anthropometry: 16% with overweight, 3% with obesity; - Physical activity: 54.8 (30.2) MET-hr/wk; - Family history of diabetes: 10%; - Smoking: NR; - Alcohol intake: 11.1 (14.1) g/d; - TEI: 2170.5 (574.5) kcal/d; - Beverage intake at baseline: 328.3 (485.8) mL/wk of SSB; 81% non-consumers; Excluded from study or analysis: baseline diabetes; missing data; extreme energy intake (lowest and highest 1% of cohort) | Exposure: SSB (excluding ASB and 100% fruit juice); - Serving Size: NR; Comparator: categorical intake (nonconsumers, <86 mL/wk, 86-164 mL/wk, 165-359 mL/wk, >359 mL/wk); Assessment methods and timing:; - Validated diet history questionnaire assessing usual intake during previous year.; - Baseline (1993); Outcome assessment methods and timing:; - Self-report in ≥1 of 8 questionnaires (validated with drug reimbursement claims or by self-reported questionnaire of biomarker concentrations); - Every 2-3y (mean follow-up: 14y (1993-2007)) | [underlined: T2D by baseline intake], HR (95% CI); Nonconsumers (n=53,538): REF; <86 mL/wk (n=4482): 1.28 (1.06, 1.55); 86-164 mL/wk (n=2699): 1.12 (0.86, 1.45); 165-359 mL/wk (n=2700): 1.22 (0.94, 1.57); >359 mL/wk (n=2699): 1.30 (1.02, 1.66); P-trend=0.0206; Stratified by BMI categories:; Nonconsumers (REF) vs >359 mL/wk; BMI <25 kg/m^2^ (n=53,695): 1.61 (1.12, 2.32); BMI between 25-30 (n=10,290): 1.22 (0.79, 1.88); BMI >30 (n=2133): 0.94 (0.56, 1.57) | Model adjustments:; - TEI: yes; - Key confounders: sex, age, socioeconomic position (years of education), anthropometry, physical activity, family history of diabetes, smoking, alcohol intake; - Other: hypertension, hypercholesterolemia, hormone replacement therapy, antidiabetic drugs, omega-3 fatty acid intake, carbohydrate intake, coffee, fruit and vegetables, processed meat intake, dietary pattern (Western or Mediterranean); Limitations:; - Did not account for key confounders: race and/or ethnicity; - Exposure only assessed at baseline; - High attrition rate/missing data with no evidence whether the result was biased due to missing data; - No preregistered data analysis plan; Funding:; Institut National du Cancer; Mutuelle Ge´ne´rale de l’Education Nationale; Institut de Cance´rologie Gustave Roussy; Institut National de la Sante´ et de la Recherche Me´dicale; European Union InterAct project
Gardener, 2018 ^19^; PCS, NOMAS (Northern Manhattan Study), U.S.; Analytic N=2,019; Study objective: To examine the relation between diet soda and regular soda consumption with the risk of incident diabetes in a longitudinal multiethnic population-based cohort; Participant characteristics at baseline: adults; - Age (mean and/or range): 69 (10y); ≥40y; - Female: 64%; - Race and/or ethnicity: 23% White; 22% Black; 2% Other; 53% Hispanic; - Socioeconomic position: NR; - Anthropometry: BMI 28 (5) kg/m^2^; - Physical activity: 10% moderate-heavy physical activity; - Family history of diabetes: NR; - Smoking: 17% current; 35% former; 48% never; - Alcohol intake: 36% moderate alcohol use; - TEI: 1569 (654) kcal/d; - Beverage intake at baseline: 14% drink regular soda ≥1/d; 45% drink regular soda <1/mo; Excluded from study or analysis: baseline diabetes; stroke; <40y;, resided in Northern Manhattan <3mo; no telephone in household; missing data; energy intake <500 or >4000 kcal/d | Exposure: Sugar-sweetened soda (regular, not diet); - Serving Size: NR; Comparator: continuous intake (number of sodas per day); categorical intake (<1/mo, 1/mo to 6/wk, daily (≥1/d)); Assessment methods and timing:; - FFQ assessing usual intake during previous year.; - Baseline; Outcome assessment methods and timing:; - Self-report of diagnosis with diabetes or high blood sugar, or use of insulin or oral hypoglycemic medications; confirmed by medical record review.; - 11 (5)y | [underlined: T2D by baseline intake], HR (95% CI); By number of regular sodas per day; Adjusted for BMI: 1.15 (1.02, 1.30); Adjusted for waist-to-hip ratio: 1.16 (1.02, 1.31); Among those with BMI <25: 1.55 (1.10, 2.19); Among those with BMI ≥25: 1.09 (0.95, 1.26); By number of regular and diet sodas per day; Adjusted for BMI: 1.14 (1.03, 1.27); Adjusted for waist-to-hip ratio: 1.18 (1.06, 1.32); By categories of regular soda consumption Adjusted for BMI; <1/mo: REF; 1/mo to 6/wk: 1.10 (0.86, 1.40); Daily: 1.13 (0.81, 1.61); Adjusted for waist-to-hip ratio; <1/mo: REF; 1/mo to 6/wk: 1.06 (0.82, 1.35); Daily: 1.11 (0.78, 1.57); Among those with BMI <25 kg/m^2^; <1/mo: REF; 1/mo to 6/wk: 0.74 (0.37, 1.45); Daily: 1.09 (0.45, 2.61); Among those with BMI ≥25 kg/m^2^; <1/mo: REF; 1/mo to 6/wk: 1.10 (0.84, 1.43); Daily: 1.09 (0.75, 1.61) | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, anthropometry, physical activity, smoking, alcohol intake; - Other: Mediterranean diet, hypertension, hypercholesterolemia; Limitations:; - Did not account for key confounders: socioeconomic position, family history of diabetes; - Exposure only assessed at baseline; - High attrition rate/missing data with no evidence whether the result was biased due to missing data; - No preregistered data analysis plan; Funding:; NIH/NINDS
Greenberg, 2005 ^20^; PCS, NHEFS (NHANES-1 Epidemiologic Follow Up Study), U.S.; Analytic N=7,006; Study objective: To assess the effect of weight change on the relationship between coffee and tea consumption and diabetes risk.; Participant characteristics at baseline: adults; - Age (mean and/or range): ~47 (0.1)y (adults ≤60y); ~72 (0.2)y (adults >60y); 32-88y; - Female: 61%; - Race and/or ethnicity: NR; - Socioeconomic position: ~34 (out of 18 educational levels between 10 and 45); ~$9000 per-capita income; - Anthropometry: BMI ~26 (0.1) kg/m^2^; - Physical activity: ~3.9 (out of 5 physical activity levels); - Family history of diabetes: 7%; - Smoking: 30% current; - Alcohol intake: 39% ≥1 drink/d; - TEI: NR; - Beverage intake at baseline: 75% overall drink cola sodas; ≤60y: ~84%; >60y: ~58%; Excluded from study or analysis: baseline diabetes; missing data | Exposure: Cola sodas (caffeinated); - Serving Size: 12oz; Comparator: continuous intake (per two 12oz svg/d increase); Assessment methods and timing:; - 3 FFQ questions on number of cups consumed, time period in which they were consumed (d, wk, mo, y), and whether beverage was consumed seasonally (assuming a 6mo season); - Baseline (1982-1984); Outcome assessment methods and timing:; - Self-reported or documented death from diabetes; - 8.4y | [underlined: T2D by baseline intake], HR (95% CI); All participants (32-88y): 1.21 (1.01, 1.45), P<0.05; ≤60y: 1.11 (0.87, 1.40), P=NS; >60y: 1.38 (1.03, 1.84), P<0.05 | Model adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position (per-capita income, educational level), anthropometry, physical activity, smoking, alcohol intake; - Other: American style diet (quintiles); Limitations:; - Did not account for key confounders: family history of diabetes; - Exposure subject to measurement error and only assessed at baseline; - No evidence whether the result was biased due to missing data; - No preregistered data analysis plan; Funding: NR
Hirahatake, 2019 ^22^; PCS, CARDIA (Coronary Artery Risk; Development in Young Adults Study), U.S.; Analytic N=4,719; Study objective: To examine the association between ASB, SSB, and total sweetened beverage consumption and T2D risk in young adults.; Participant characteristics at baseline: Black and White adults; - Age (mean and/or range): 25 (3)y; 18-30y; - Female: 55%; - Race and/or ethnicity: 50% White; 50% Black; - Socioeconomic position: ~15y education attained through follow-up; - Anthropometry: BMI 24 (5) kg/m^2^; - Physical activity: ~200 min/wk of moderate-intensity activity; - Family history of diabetes: 16%; - Smoking: 29% current; 13% former; 58% never; - Alcohol intake: ~12 mL/d; - TEI: ~2700 kcal/d; - Beverage intake at baseline: 45% drink SSB ≥1/d; mean intake: 1.38 (1.7) svg/d; Excluded from study or analysis: baseline diabetes; missing data; loss to follow-up; energy intake <600 kcal or >6000 kcal/d for women, <800 or >8000 kcal/d for men | Exposure: SSB (sugar-sweetened soft drinks and fruit drinks); - Serving Size: 8oz; Comparator: continuous intake (svg/d); categorical intake (none to <1 svg/wk, 1 to <4 svg/wk, 4 to <7/wk, 1-2 svg/d, >2 svg/d); Assessment methods and timing:; - Validated diet history questionnaire on diet during previous month. A cumulative average intake value was calculated for each participant based on dietary data collected at different time points.; - Baseline, 7y and 20y follow-up; Outcome assessment methods and timing:; - Biomarkers; - 25.3 (8.3)y (years 0, 7, 10, 15, 20, 25, 30) | [underlined: T2D by cumulative average SSB,] HR (95% CI); None to ≤ 1/wk: REF; 1 to ≤4/wk: 0.98 (0.73, 1.31); 4 to ≤7/wk: 0.97 (0.71, 1.32); 1-2/d: 0.96 (0.71, 1.29); ≥2/d: 1.27 (0.93, 1.74); Quintile 1: REF; Quintile 2: 0.98 (0.73, 1.31); Quintile 3: 0.97 (0.71, 1.32); Quintile 4: 0.96 (0.71, 1.29); Quintile 5: 1.27 (0.93, 1.74); Per svg/d: 1.06 (1.01, 1.10), P=0.009; Results were also consistent in the subset of population with data on family history of diabetes (data NR); Stratified analyses:; Men: 1.10 (1.03, 1.18); Women: 1.02 (0.97, 1.08); P-interaction (sex)=0.66; Black: 1.05 (1.00, 1.10); White: 1.10 (1.02, 1.19); P-interaction (race)=0.014; BMI ≤24.9 kg/m^2^: 1.08 (1.00, 1.17); BMI 25.0-29.9 kg/m^2^: 1.09 (1.02, 1.17); BMI ≥30 kg/m^2^: 1.04 (0.98, 1.11); P-interaction (BMI)=0.06 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position (time-updated measures of education), anthropometry, physical activity, family history of diabetes, smoking, alcohol intake; - Other: CARDIA center, other beverage intake, dieting behavior, average alternate Mediterranean diet score; Limitations:; - No evidence whether the result was biased due to missing data; - No preregistered data analysis plan; Funding: NHLBI
Huang, 2017 ^23^; PCS, Women’s Health Initiative, U.S.; Analytic N=64,850; Study objective: To evaluate the associations of ASB and SSB consumption with the risk of developing T2D and the potential benefit of replacing SSBs with ASBs or water.; Participant characteristics at baseline: postmenopausal women; - Age (mean and/or range): ~63y; 50-79y; - Female: 100%; - Race and/or ethnicity: 87% Non-Hispanic White; 6% African American; 4% Other; 3% Hispanic/Latino; - Socioeconomic position: 28% ≤high school, 27% some college or associate degree, 45% college or higher; 11% with annual family income <$20k, 38% with $20k-<$50k, and 45% with ≥$50k (6% missing income data); 2% no health insurance; - Anthropometry: BMI ~27 (5) kg/m^2^; 36% with overweight, 24% with obesity; - Physical activity: 19% <1.8 MET hr/wk, 55% 1.8-20 MET hr/wk, 26% >20 MET hr/wk; - Family history of diabetes: 30%; - Smoking: 4% current; 44% former; 52% never; - Alcohol intake: ~5.7 g/d; - TEI: ~2300 kcal/d; - Beverage intake at baseline: SSB ~0.5 svg/d (31% <1 svg/wk); Excluded from study or analysis: baseline diabetes; missing data; BMI <18.5 kg/m^2^, energy intake <600 or >5000 kcal/d | Exposure: SSB (regular/non-diet soda and soft drinks, fruit juice, and fruit drinks); fruit juice included “orange juice and grapefruit juice”, and “other fruit juices such as apple and grape”; fruit drinks included “Tang, Kool-Aid, Hi-C, and other fruit drinks”; - Serving Size: 355mL (one 12oz can); Comparator: continuous intake (every 12oz increase); categorical intake (<1 svg/wk, 1 to <7 svg/wk, 1 to <2 svg/d, ≥2 svg/d); Assessment methods and timing:; - FFQ on intake during the past 3 months.; - Baseline; Outcome assessment methods and timing:; - Self-report: answered yes when asked if “a doctor prescribed for the first time any of the following pills or treatments: pills for diabetes or insulin shots for diabetes”; validated by medical record review and laboratory data; - 8.4y (annually) | [underlined: T2D by baseline intake], HR (95% CI); Per 12oz increase in SSB: 1.13 (1.07, 1.20); Total SSB; <1 svg/wk: REF; 1 to <7 svg/wk: 1.05 (0.98, 1.12); 1 to <2 svg/d: 1.09 (0.97, 1.23); ≥2 svg/d: 1.43 (1.17, 1.75); P-trend=0.0004; Regular soda; <1 svg/wk: REF; 1 svg/wk to <1 svg/d: 1.12 (1.02, 1.22); ≥1 svg/d: 1.12 (0.97, 1.29); Fruit drinks; <1 svg/wk: REF; 1 svg/wk to <1 svg/d: 0.99 (0.85, 1.15); ≥1 svg/d: 1.33 (0.89, 1.98) | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position (family income; education; insurance status), anthropometry, physical activity, family history of diabetes, smoking, alcohol intake; - Other: systolic blood pressure, antihypertensive use, antihyperlipidemic use, hormone replacement therapy use, other beverage consumption, glycemic load and index, AHEI, cardiovascular history, hysterectomy history, sitting time; Limitations:; - Exposure only assessed at baseline; - High attrition rate/missing data; - No preregistered data analysis plan; Funding: NHLBI
Imamura, 2019 ^24^; PCS, EPIC-InterAct, 8 European countries; (France, Italy, Spain, UK, The Netherlands, Germany, Sweden, and Denmark); Analytic N=27,662 (subcohort = 16,103); Study objective: To estimate the risk of T2D when consumption of SSB was replaced with consumption of fruit juice, milk, coffee, or tea.; Participant characteristics at baseline: adults; - Age (mean and/or range): ~54y; - Female: 58%; - Race and/or ethnicity: NR; - Socioeconomic position: 18% >high school education; 50% currently employed; - Anthropometry: BMI ~28 kg/m^2^; - Physical activity: 42% ≥moderately active; - Family history of diabetes: 30%; - Smoking: 28% current; - Alcohol intake: ~210 mL/d; - TEI: ~2150 (715) kcal/d; - Beverage intake at baseline: 55 (105) g/d of SSB; 6% consume ≥250 g/day of SSB; Excluded from study or analysis: baseline diabetes; missing data | Exposure: SSB (carbonated/soft/isotonic drinks, diluted syrups, sweetened or unspecified, containing >2g carbohydrates per 100g, and sweetened milk beverages); artificially-sweetened beverages were not separated out in some centers, and sweetened milk beverages were assessed in limited regions; - Serving Size: NR; Comparator: continuous intake (per 250 g/d); Assessment methods and timing:; - FFQ or dietary questionnaire (country-specific) assessing usual intake during previous year.; - Baseline; Outcome assessment methods and timing:; - Combination of self-report, linkage to registries, hospital/mortality data; - Median 6y | [underlined: T2D by baseline intake], HR (95% CI); Per 250 g/d of SSB: 1.18 (1.08, 1.28); Not including sweetened milk beverages: 1.16 (1.07, 1.27) | Model adjustments:; - TEI: yes; - Key confounders: sex, age, socioeconomic position (education, marital status), anthropometry, physical activity, family history of diabetes, smoking, alcohol intake; - Other: research center, hormone replacement therapy, menopausal status, history of oral contraceptive use, hypertension, dyslipidemia, coronary heart disease, stroke, dietary supplement use, dietary consumption (vegetables, fruit, nuts, cheese, yogurt, red meats, processed meats, fish, confectionary, cereals, other beverages); Limitations:; - Did not account for key confounders: race and/or ethnicity; - Exposure subject to measurement error and only assessed at baseline; - No evidence whether the result was biased due to missing data; - No preregistered data analysis plan; Funding:; EU FP6 Programme
Jahromi, 2023 ^26^; PCS, Tehran Lipid and Glucose Study, Iran; Analytic N=2,081; Study objective: To assess the association of dietary diabetes risk reduction scores (DDRRS) with T2D risk in Iranian adults; Participant characteristics at baseline: Iranian adults; - Age (mean and/or range): 50.4 (8.2)y; ≥40y; - Female: 53%; - Race and/or ethnicity: NR; - Socioeconomic position: 19% academic education; 84% employed; - Anthropometry: BMI 28.3 (4.3) kg/m^2^; - Physical activity: ~67 MET hr/wk; - Family history of diabetes: 10%; - Smoking: 12% current; - Alcohol intake: NR; - TEI: ~2300 kcal/d; - Beverage intake at baseline: Mean: ~1.2 svg/wk of SSB; Excluded from study or analysis: baseline diabetes; <40y; missing data; loss to follow-up; energy intakes <800 or >4200 kcal/d or those on specific diets; history of cancer or CVD; pregnant or lactating | Exposure: Sugar-sweetened beverages; - Serving Size: NR; Comparator: categorical intake (tertiles in svg/wk); - Tertile 1: assigned a score of 4 points in DDRRS (highest intake); - Tertile 3: assigned a score of 1 point in DDRRS; Assessment methods and timing:; - FFQ assessing usual intake during previous year. Participants were categorized into quartiles based on their intake ranking. For SSB, participants in the lowest quartile were assigned a score of 4 points and those in the highest quartile were assigned 1 point.; - Baseline; Outcome assessment methods and timing:; - Biomarkers (FPG ≥126 mg/dL or 2h post-75g glucose load ≥200 mg/dL) or medication; - 6y | [underlined: T2D by baseline intake], OR (95% CI); Tertile 1 (highest intake): REF; Tertile 2: 0.74 (0.53, 1.03); Tertile 3: 0.49 (0.32, 0.76); P-trend=0.002 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, socioeconomic position (educational level; occupation status; marital status), anthropometry, physical activity, smoking; - Other: baseline FPG; Limitations:; - Did not account for key confounders: race and/or ethnicity, family history of diabetes, alcohol intake; - Exposure only assessed at baseline; - No evidence whether the result was biased due to missing data; - No preregistered data analysis plan; Funding:; Shahid Beheshti University of Medical Sciences
McNaughton, 2008 ^28^; PCS, Whitehall-II, UK; Analytic N=6,699; Study objective: To identify a dietary pattern associated with insulin resistance and investigate whether this pattern was prospectively associated with T2D; Participant characteristics at baseline: adults; - Age (mean and/or range): 49.5 (0.1)y; 39-63y; - Female: 30%; - Race and/or ethnicity: 90% Caucasian; - Socioeconomic position: 16% low employment grade (out of 6 levels); - Anthropometry: BMI 25.3 (0.0) kg/m^2^; - Physical activity: vigorous activity 1.1 (0.0) times/wk; - Family history of diabetes: NR; - Smoking: 14% current; - Alcohol intake: 12.1 (0.2) g/d; - TEI: NR; - Beverage intake at baseline: ~58 g/d SSB; Excluded from study or analysis: baseline diabetes; missing data; loss to follow-up | Exposure: SSB dietary patterns factor identified from RRR; - Serving Size: NR; Comparator: categorical intake (based on quartiles of overall dietary pattern score) SSB intake (g/d), Mean (SE):; - Quartile 1: 37.3 (1.6); - Quartile 2: 49.7 (1.8); - Quartile 3: 65.5 (2.2); - Quartile 4: 112.8 (4.1); Assessment methods and timing:; - FFQ assessing usual intake during previous year.; - Baseline (1993); Outcome assessment methods and timing:; - Self-report based on doctor’s diagnosis or diabetic medication; confirmed with 2hr OGTT; - 11.6y (Phases 5 (1996-1997) and 7 (2004)) | [underlined: T2D by baseline intake], HR (95% CI); By quartiles of SSB intake: Data not shown; P-trend=NS | Model adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position (employment grade), anthropometry, physical activity, smoking, alcohol intake; - Other: blood pressure, energy misreporting (ratio of total energy intake to energy expenditure, 1 or <1); Limitations:; - Did not account for key confounders: family history of diabetes; - Exposure subject to measurement error and only assessed at baseline; - High attrition rate/missing data with no evidence whether the result was biased due to missing data; - No preregistered data analysis plan; Funding:; UK Medical Research Council; British Heart Foundation; Health and Safety Executive (UK); Department of Health; NHLBI; NIA; Agency for Health Care Policy Research; MacArthur Foundation Research Network on Socioeconomic Status and Health
Montonen, 2007 ^29^; PCS, Finnish Mobile Clinic Health Examination, Finland; Analytic N=2360 (soft drinks); 4304 (sweetened berry juice); Study objective: To examine the association between intakes of different sugars and the incidence of T2D in a large nationwide cohort of Finns; Participant characteristics at baseline: adults; - Age (mean and/or range): ~53y; 40-69y; - Female: 47%; - Race and/or ethnicity: NR; - Socioeconomic position: NR; - Anthropometry: BMI ~27 kg/m^2^; - Physical activity: 58% physically active; - Family history of diabetes: 20%; - Smoking: 33% current; - Alcohol intake: NR; - TEI: ~2500 kcal/d; - Beverage intake at baseline: ~66 g/d soft drinks; ~23 g/d of sweetened berry juice; Excluded from study or analysis: baseline diabetes; <40 or >69y; energy intake <800 or >6000 kcal/d | Exposure: Soft drinks; Sweetened berry juice; - Serving Size: NR; Comparator: categorical intake (quartiles); Median intake for quartiles 1, 2, 3, 4; - Soft drinks: 0, 1, 13, 143 g/d; - Sweetened berry juice: 0, 7.5, 21, 51 g/d; Assessment methods and timing:; - Diet history interview assessing usual diet during previous year.; - Baseline; Outcome assessment methods and timing:; - National registries; - 12y | [underlined: T2D by baseline intake], RR (95% CI); Soft drink intake; Quartile 1 (n=741): REF; Quartile 2 (n=458): 0.85 (0.42, 1.73); Quartile 3 (n=573): 0.80 (0.43, 1.49); Quartile 4 (n=588): 1.60 (0.93, 2.76); P-trend=0.01; Sweetened berry juice intake; Quartile 1 (n=1665): REF; Quartile 2 (n=726): 0.68 (0.41, 1.14); Quartile 3 (n=802): 0.95 (0.60, 1.49); Quartile 4 (n=1091): 1.56 (1.08, 2.26); P-trend=0.006 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, anthropometry, physical activity, family history of diabetes, smoking; - Other: geographic area, prudent dietary score, conservative pattern score, serum cholesterol, blood pressure; history of infarction, angina pectoris, and cardiac failure; Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position, alcohol intake; - Exposure only assessed at baseline; - No evidence whether the result was biased due to missing data; - No preregistered data analysis plan; Funding:; NR
Nettleton, 2009 ^30^; PCS, MESA (Multi-Ethnic Study of Atherosclerosis), U.S.; Analytic N=5,011; Study objective: To determine associations between diet soda consumption and risk of incident metabolic syndrome, its components, and T2D; Participant characteristics at baseline: adults; - Age (mean and/or range): ~61y; 45-84y; - Female: 53%; - Race and/or ethnicity: 43% White; 23% African American; 12% Chinese; 21% Hispanic; - Socioeconomic position: 85% high school degree; - Anthropometry: BMI 27.9 kg/m^2^; - Physical activity: ~2400 MET-min/wk; - Family history of diabetes: NR; - Smoking: 14% current; - Alcohol intake: NR; - TEI: ~1700 kcal/d; - Beverage intake at baseline: 14% drink SSB ≥1 svg/d; 45% never drink SSB; Excluded from study or analysis: baseline diabetes; insufficient or implausible dietary information | Exposure: Sugar-sweetened soda (“regular soft drinks, soda, sweetened mineral water (not diet), nonalcoholic beer”); - Serving Size: small, medium, or large (weighted as intake frequency × 0.5, × 1.0, and × 1.5 for small, medium, and large, respectively); Comparator: categorical intake (Rare/never, >Rare/never but <1 svg/wk, ≥1 svg/wk to <1 svg/d, ≥1 svg/d); Assessment methods and timing:; - FFQ assessing usual intake during previous year.; - Baseline; Outcome assessment methods and timing:; - Self-report, fasting glucose ≥126 mg/dl at any exam, or use of antidiabetes medication; - 5.8y (baseline at 2000-2002 and 3 follow-up exams conducted from 2002-2003, 2004-2005, and 2005-2007) | [underlined: T2D by baseline intake], HR (95% CI); Rare/never: REF; >Rare/never but <1 svg/wk: Data NR; ≥1 svg/wk to <1 svg/d: Data NR; ≥1 svg/d: Data NR; P-trend=NS | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position (education), anthropometry, physical activity, smoking; - Other: dietary supplement use; Limitations:; - Did not account for key confounders: family history of diabetes, alcohol intake; - Exposure only assessed at baseline; - High attrition rate/missing data with no evidence whether the result was biased due to missing data; - No preregistered data analysis plan; Funding:; NHLBI
O’Connor, 2016 ^31^; PCS, EPIC-Norfolk, UK; Analytic N=24,653; Study objective: To evaluate the association of types of SSB, ASB, and fruit juice with incident T2D; Participant characteristics at baseline: adults; - Age (mean and/or range): 58.7 (9.3)y; 40-79; - Female: 55%; - Race and/or ethnicity: Primarily White European; - Socioeconomic position: 13% university degree; 44% professional or managerial social class; - Anthropometry: BMI 26.3 (3.9) kg/m^2^; 45% with overweight, 15% with obesity; - Physical activity: 18% active (based on 4-level index); - Family history of diabetes: 13%; - Smoking: 12% current; - Alcohol intake: 3.5 (1-10) units/wk; - TEI: 1950 (508) kcal/d; - Beverage intake at baseline: 30% SSB consumers, 83 (41-176) g/d; Excluded from study or analysis: baseline diabetes or unconfirmed status; missing data on diet or covariates; extreme energy intake (top and bottom 1%) | Exposure: Sugar-sweetened soft drinks (soft drinks, sports/energy drinks, and squashes sweetened with sugar, and juice-based beverages); - Serving Size: 336 g (12oz); Comparator: continuous intake (per 336 g svg); categorical intake (non-consumers and consumers in tertiles); Tertiles (range and median intake, g/d); - Tertile 1: >0-49 (35); - Tertile 2: 50-139 (83); - Tertile 3: 140-3172 (234); Assessment methods and timing:; - 7d food diary; - Baseline; Outcome assessment methods and timing:; - Self-report; verified using data internal and external to study through record linkage; - 10.8y | [underlined: T2D by baseline intake], HR (95% CI); Non-consumers: REF; Tertile 1: 0.97 (0.80, 1.18); Tertile 2: 0.98 (0.80, 1.19); Tertile 3: 1.13 (0.94, 1.36); P-trend=0.306; Per svg (336 g): 1.14 (1.01, 1.32); Subgroup analyses:; P-interaction (age)≥0.483; P-interaction (sex)≥0.090; P-interaction (BMI)≥0.424; P-interaction (waist)≥0.182; P-interaction (physical activity)≥0.099; P-interaction (smoking)≥0.274 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, socioeconomic position (occupational social class; educational level), anthropometry, physical activity, family history of diabetes, smoking, alcohol intake; - Other: season (winter/summer), intake of other sweet beverages, fiber intake, saturated fat intake; Limitations:; - Did not account for key confounders: race and/or ethnicity; - Exposure only assessed at baseline; - No preregistered data analysis plan; Funding:; Medical Research Council UK; Cancer Research UK
Odegaard, 2010 ^32^; PCS, Singapore Chinese Health study, Singapore; Analytic N=43,580; Study objective: To investigate the nature of the association between consumption of soft drinks and juices and the risk of incident T2D; Participant characteristics at baseline: Chinese Singaporean adults; - Age (mean and/or range): 54.8 (7.5)y; 45-74y; - Female: 57%; - Race and/or ethnicity: All Chinese; - Socioeconomic position: 34% secondary education; - Anthropometry: BMI ~23 kg/m^2^; - Physical activity: ~50 min/wk moderate activity; - Family history of diabetes: NR; - Smoking: 27% ever; - Alcohol intake: ~1 drink/wk; - TEI: ~1600 kcal/d; - Beverage intake at baseline: 74% never; 11% ≥2x/wk; Excluded from study or analysis: baseline diabetes or unclear status; cancer, heart disease, stroke; energy intakes <600 or >5000 kcal/d; loss to follow-up; not Hokkien or Cantonese dialect groups | Exposure: Soft drinks, such as Coca Cola and 7UP; - Serving Size: 1 glass = 237 mL (~1 cup); Comparator: categorical intake (almost never; 1-3x/mo; 1x/wk; ≥2x/wk); Assessment methods and timing:; - FFQ assessing usual intake during previous year.; - Baseline; Outcome assessment methods and timing:; - Self-report of physician-diagnosed diabetes; validated with records; - 5.7y | [underlined: T2D by baseline intake], RR (95% CI); Almost never (n=32,060): REF; 1-3x/mo (n=4514): 1.11 (0.97, 1.26); 1x/wk (n=2389): 0.98 (0.81, 1.29); ≥2x/wk (n=4617): 1.34 (1.17, 1.52); P-trend<0.0001; NS effect modification by sex, age, or BMI | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position (educational level), anthropometry, physical activity, smoking, alcohol intake; - Other: year of interview, saturated fat, dietary fiber, dairy, juice, coffee; Limitations:; - Did not account for key confounders: family history of diabetes; - Exposure only assessed at baseline; - No evidence whether the result was biased due to missing data; - No preregistered data analysis plan; Funding:; NIH
Olsson, 2021 ^33^; PCS, Malmö Diet and Cancer, Sweden; Analytic N=26,622; Study objective: To analyze associations between intakes of 6 types of carbohydrates and thirteen carbohydrate-rich foods with incident T2D; Participant characteristics at baseline: middle-aged and older adults; - Age (mean and/or range): ~58y; - Female: 61%; - Race and/or ethnicity: NR; - Socioeconomic position: 14% university degree; - Anthropometry: BMI ~26 kg/^2^; - Physical activity: 10% with <7.5 METhr/wk of leisure-time physical activity; - Family history of diabetes: NR; - Smoking: 28% current; - Alcohol intake: 6% zero consumers; - TEI: ~2645 kcal/d in men, ~2020 kcal/d in women; - Beverage intake at baseline: SSB ~96 g/d in men, ~71 g/d in women; Excluded from study or analysis: baseline diabetes; missing data; limited Swedish proficiency and mental disability | Exposure: SSB (all carbonated and noncarbonated beverages; except juices, dairy products, and alcohol beverages); - Serving Size: NR; Comparator: categorical intake (nonconsumers vs tertiles); - Non-consumers (n=12,066); - Tertile 1 (n=5103): 0.3-47.1 g/d; - Tertile 2 (n=4596): 47.3-142.8 g/d; - Tertile 3 (n=4857): 142.9-3000.0 g/d; Assessment methods and timing:; - Validated, modified diet history (7d food diary, FFQ assessing usual intake during previous year, and 60min interview); - Baseline; Outcome assessment methods and timing:; - National registries; rescreening of cohort; - 18.4 (6.4)y | [underlined: T2D by baseline intake], HR (95% CI); By g/d of SSB:; All Participants; Non-consumers: REF; Tertile 1: 1.02 (0.94, 1.12); Tertile 2: 1.05 (0.96, 1.15); Tertile 3: 1.05 (0.96, 1.14); P-trend=0.23; P-interaction (sex)=0.35; Men; Non-consumers: REF; Tertile 1: 0.97 (0.86, 1.11); Tertile 2: 1.00 (0.88, 1.14); Tertile 3: 1.00 (0.89, 1.13); P-trend=0.92; Women; Non-consumers: REF; Tertile 1: 1.04 (0.92, 1.17); Tertile 2: 1.09 (0.97, 1.23); Tertile 3: 1.06 (0.94, 1.20); P-trend=0.20; By g/1000 kcal of SSB: All Participants; Non-consumers: REF; Tertile 1: 1.02 (0.93, 1.11); Tertile 2: 1.06 (0.97, 1.16); Tertile 3: 1.04 (0.95, 1.13); P-trend=0.24; P-interaction (sex)=0.59 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, socioeconomic position (education), anthropometry, physical activity, smoking, alcohol intake; - Other: diet method version, season of diet collection, coffee, meat, whole grains; Limitations:; - Did not account for key confounders: race and/or ethnicity, family history of diabetes; - Exposure only assessed at baseline; - No evidence whether the result was biased due to missing data; - No preregistered data analysis plan; Funding:; Swedish Research Council; Swedish Heart-Lung Foundation; Albert Påhlsson Foundation; Swedish Foundation for Strategic Research
Palmer, 2008 ^34^; PCS, Black Women’s Health Study, U.S.; Analytic N=43,960; Study objective: To examine the association between consumption of sugar-sweetened beverages, weight gain, and incidence of T2D in African American women; Participant characteristics at baseline: African American women; - Age (mean and/or range): ~38 (10)y; 21-69y; - Female: 100%; - Race and/or ethnicity: 100% African American; - Socioeconomic position: 15% education ≤12y; - Anthropometry: BMI ~28 (7) kg/m^2^; - Physical activity: 50% with ≥1 hr/wk; - Family history of diabetes: 34%; - Smoking: 16% current; - Alcohol intake: ~1.4 (4) drinks/wk; - TEI: ~1700 (650) kcal/d; - Beverage intake at baseline: 17% drank ≥1/d sugar-sweetened soft drink; 32% drank ≥1/d sweetened fruit drink; Excluded from study or analysis: baseline diabetes; GDM, myocardial infarction, stroke, or cancer; pregnant; <30y at the end of followup; missing data; energy intake <500 or >3800 kcal/d | Exposure: Sugar-sweetened soft drinks (“regular soft drinks, not diet soda”); sweetened fruit drinks (“fortified fruit drinks, Kool-Aid, and fruit juices other than orange or grapefruit juice”); - Serving Size: Soft drinks: 12 oz (336g); Fruit drinks: 6 oz (168 g); Comparator: categorical intake (<1 drink/mo, 1-7 drinks/mo, 2-6 drinks/wk, 1 drink/d, ≥2 drinks/d); Assessment methods and timing:; - FFQ; - Baseline (1995), 6y follow-up (2001) - only baseline used in analyses; Outcome assessment methods and timing:; - Self-report via biennial questionnaire; - 10y | [underlined: T2D by baseline intake], HR (95% CI); Sugar-sweetened soft drinks; <1 drink/mo: REF; 1-7 drinks/mo: 0.89 (0.80, 0.99); 2-6 drinks/wk: 1.00 (0.89, 1.12); 1 drink/d: 1.11 (0.96, 1.28); ≥2 drinks/d: 1.24 (1.06, 1.45); 1.05 (0.90, 1.23) when adjusting for BMI, 1.04 when adjusting for TEI; P-trend=0.002; Sweetened fruit drinks; <1 drink/mo: REF; 1-7 drinks/mo: 1.08 (0.96, 1.22); 2-6 drinks/wk: 1.08 (0.96, 1.21); 1 drink/d: 1.17 (1.02, 1.33); ≥2 drinks/d: 1.31 (1.13, 1.52); 1.33 (1.15, 1.54) when adjusting for BMI, 1.32 when adjusting for TEI; P-trend=0.001; Also provided analyses stratified by age (<40y and ≥40y), BMI (<25, 25-29, and ≥30 kg/m^2^), and family history of diabetes - weak positive association between highest category of sweetened fruit drink consumption and risk of T2D across subgroups for each factor except BMI <25 kg/m^2^ | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position (years of education), anthropometry, physical activity, family history of diabetes, smoking; - Other: diet (red meat, processed meat, cereal fiber, other beverages), glycemic index, questionnaire cycle; Limitations:; - Did not account for key confounders: alcohol intake; - Analyses based on exposure collected only at baseline; - High attrition rate/missing data with no evidence whether the result was biased due to missing data; - Outcome was self-reported; - No preregistered data analysis plan; Funding:; NCI; NIDDK
Pan, 2012 ^35^; PCS, NHS-II (Nurses’ Health Study II), U.S.; Analytic N=82,902; Study objective: To evaluate the relation of plain-water intake and the substitution of plain water for SSB and fruit juice with incident T2D in U.S. women; Participant characteristics at baseline: women; - Age (mean and/or range): 36.0 (4.7)y; 26-45y; - Female: 100%; - Race and/or ethnicity: Primarily European ancestry; - Socioeconomic position: All nurses; - Anthropometry: BMI ~24 (5) kg/m^2^; - Physical activity: ~19 METs/wk; - Family history of diabetes: 33%; - Smoking: 12% current; - Alcohol intake: ~3 g/d; - TEI: ~1800 kcal/d; - Beverage intake at baseline: NR; Excluded from study or analysis: baseline diabetes; cancer or cardiovascular disease; missing data; implausible total energy intake (<500 or >3500 kcal/d) | Exposure: SSB (Coke, Pepsi, or other cola with sugar; other carbonated beverages with sugar; and Hawaiian Punch, lemonade, or other noncarbonated fruit drinks); - Serving Size: 1 cup = 240mL; Comparator: continuous intake (svg/d) categorical intake (≤1 cup/wk, 2-4 cups/wk, 5-7 cups/wk, 2-3 cups/d, ≥4 cups/d); Assessment methods and timing:; - FFQ assessing usual intake during previous year.; - 1991, 1995, 1999, 2003 (cumulative average intake); Outcome assessment methods and timing:; - Self-reported via biennial questionnaire; verified with supplementary questionnaire specific to T2D; - Up to 2009 | [underlined: T2D by cumulative average intake], RR (95% CI); ≤1 cup/wk: REF; 2-4 cups/wk: 1.10 (0.99, 1.22); 5-7 cups/wk: 1.22 (1.10, 1.36); 2-3 cups/d: 1.34 (1.19, 1.51); ≥4 cups/d: 1.29 (1.07, 1.54); P-trend<0.001; Per 1 svg/d: 1.09 (1.05, 1.14) | Model adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, anthropometry, physical activity, family history of diabetes, smoking, alcohol intake; - Other: menopausal status and hormone use, oral contraceptive use, AHEI; Limitations:; - Did not account for key confounders: socioeconomic position; - No evidence whether the result was biased due to missing data; - No preregistered data analysis plan; Funding:; NIH
Paynter, 2006 ^36^; PCS, ARIC (Atherosclerosis Risk in Communities Study), U.S.; Analytic N=12,204; Study objective: To examine the association between coffee and sweetened beverage consumption in a US community-based cohort of middle-aged Black and White men and women; Participant characteristics at baseline: Black and White adults; - Age (mean and/or range): 54y; 45-64y; - Female: 56%; - Race and/or ethnicity: 78% White; 22% Black; - Socioeconomic position: 20% less than high school education; - Anthropometry: BMI 27.2 kg/m^2^; 24% with obesity; - Physical activity: ~2.4 leisure activity index (out of 5, with 1 indicating least active); - Family history of diabetes: 24% Women; 21% Men; - Smoking: Women: 24% current, 53% never; Men: 26% current, 29% never; - Alcohol intake: 59% consumers; - TEI: ~1750 kcal/d (men), ~1500 kcal/d (women); - Beverage intake at baseline: 15% drink ≥2 cups/d; Excluded from study or analysis: baseline diabetes; reported ethnicity other than Black or White; missing data; loss to follow-up | Exposure: Sweetened beverages (fruit punch, non-diet soda, and orange or grapefruit juice); - Serving Size: 1 cup = 0.24 L; Comparator: categorical intake (<1, 1, 1.1-1.9, ≥2 cups/d); Assessment methods and timing:; - FFQ assessing usual intake during previous year.; - Baseline; Outcome assessment methods and timing:; - Combination of self-report of physician-diagnosed diabetes, diabetes treatment, and a fasting or nonfasting blood glucose test; - Maximum 9y | [underlined: T2D by baseline intake], HR (95% CI); Men; <1 cup/d: REF; 1 cup/d: 1.03 (0.79, 1.34); 1.1-1.9 cup/d: 0.95 (0.79, 1.15); ≥2.0 cup/d: 1.03 (0.82, 1.28); P-trend=0.94; Women; <1 cup/d: REF; 1 cup/d: 1.13 (0.91, 1.42); 1.1-1.9 cup/d: 1.10 (0.91, 1.33); ≥2.0 cup/d: 1.01 (0.79, 1.29); P-trend=0.58; Stratification by age, BMI, or physical activity did not affect results, nor did removing juice from definition of sweetened beverages (data NR) | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position (education), anthropometry, physical activity, family history of diabetes, smoking, alcohol intake; - Other: dietary fiber, hypertension; Limitations:; - Exposure only assessed at baseline; - High attrition rate/missing data; - No preregistered data analysis plan; Funding:; NHLBI
Ramne, 2020 ^37^; PCS, Malmö Diet and Cancer-Cardiovascular Cohort (MDC-CC), Sweden; Analytic N=4,382; Study objective: To examine how added sugar and SSB intake associate with 136 measured plasma proteins and C-reactive protein, and examine if the identified added sugar- and SSB-associated proteins associate with T2D incidence.; Participant characteristics at baseline: middle-aged and older adults; - Age (mean and/or range): 57y; 45-68y; - Female: 62%; - Race and/or ethnicity: NR; - Socioeconomic position: 12% university degree; - Anthropometry: BMI 25.5 kg/m^2^; - Physical activity: NR; - Family history of diabetes: NR; - Smoking: 26% current; - Alcohol intake: 16% highest quintile of consumers; - TEI: ~2300 kcal/d; - Beverage intake at baseline: 46% reported no SSB intake on 7d food record; median contribution of SSB to added sugar intake: <1%; Excluded from study or analysis: baseline diabetes or cardiovascular disease; missing data | Exposure: SSB as a percentage of energy intake (which was estimated assuming SSB have a mean sugar content of 10g per 100g and the sugar content in soft drinks varies between 10-13g per 100g and cordial/squash contains ~8g per 100g); - Serving Size: NR; Comparator: categorical intake (0%, >0-2%, >2–3%, >3–5%, >5% of energy intake); Assessment methods and timing:; - Validated, modified diet history (7d food diary, FFQ assessing usual intake during previous year, and 60-min interview); - Baseline; Outcome assessment methods and timing:; - National registries; - NR | [underlined: T2D by baseline intake], HR (95% CI); By SSB intake as a % of energy intake; 0% (n=2039): REF; >0-2% (n=1471): 1.10 (0.93, 1.29); >2–3% (n=310): 1.06 (0.79, 1.42); >3–5% (n=307): 1.05 (0.78, 1.40); >5% (n=255): 1.19 (0.88, 1.60); HR-trend: 1.03 (0.97, 1.10); P-trend=0.28 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, socioeconomic position (education), physical activity, smoking, alcohol intake; - Other: season, screening date; Limitations:; - Did not account for key confounders: race and/or ethnicity, anthropometry, family history of diabetes; - Exposure only assessed at baseline; - No information on start of follow-up; - No evidence whether the result was biased due to missing data; - No preregistered data analysis plan; Funding:; Swedish Research Council; Heart and Lung Foundation; Albert Påhlsson Foundation
Rhee, 2015 ^38^; PCS, NHS (Nurses’ Health Study) and NHS-II, U.S.; Analytic N=162,416; Study objective: To evaluate racial and ethnic differences in the association between a dietary diabetes risk reduction score and incidence of type 2 diabetes in U.S. white and minority women.; Participant characteristics at baseline: women; - Age (mean and/or range): 40 (7)y; 34-59y (NHS-I); 27-44y (NHS-II); - Female: 100%; - Race and/or ethnicity: 96% White (including non-Hispanic White); 1.4% Black; 1.2% Asian; 1.3% Hispanic; - Socioeconomic position: All nurses; - Anthropometry: BMI kg/m^2^, White: 24.4 (5), Black: 26.5 (6), Asian: 22.6 (4), Hispanic: 24.8 (5); - Physical activity: MET-hr/wk, White: 17 (24), Black: 16 (25), Asian: 17 (27), Hispanic: 20 (31); - Family history of diabetes: 31% White, 45% Black, 40% Asian, 43% Hispanic; - Smoking: current: 19% White, 18% Black, 8% Asian, 11% Hispanic; - Alcohol intake: 4.6 (8.4) g/d in White women (1.6-3.6 g/d in other racial and ethnic groups, P<0.05 compared to White); - TEI: ~1700 kcal/d; - Beverage intake at baseline: SSB 0.39 (0.75) svg/d in White women (0.45-0.68 svg/d in other racial/ethnic groups, p<0.05 compared to White); Excluded from study or analysis: baseline diabetes; cancer or cardiovascular disease; missing data; loss to follow-up; energy intake <500 or >3500 kcal/d | Exposure: SSB (Coke, Pepsi, or other cola with sugar; other carbonated beverages with sugar; and Hawaiian Punch, lemonade, or other noncarbonated fruit drinks); - Serving Size: NR; Comparator: continuous intake (increase of 1 svg/d); Assessment methods and timing:; - FFQ assessing usual intake during previous year.; - Baseline (1980 in NHS, 1991 in NHS-II) and every 4y for up to 18y (NHS II) or 28y (NHS); Outcome assessment methods and timing:; - Self-reported via biennial questionnaire; verified with supplementary questionnaire specific to T2D; - Maximum 18y (up to 2009 in NHS-II) and 28y (up to 2008 in NHS) | [underlined: T2D by cumulative average intake over follow up], HR (95% CI); Per 1 svg/d increase in SSB; Non-Hispanic White women (n=156,030); NHS: 1.42 (1.28, 1.57); NHS-II: 1.15 (1.07, 1.25); Pooled: 1.25 (1.17, 1.33); Minority (Asian, Hispanic, and Black) women (n=6386); NHS: 1.51 (1.01, 2.27); NHS-II: 1.01 (0.73, 1.24); Pooled: 1.16 (1.08, 1.25) | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, anthropometry (BMI in sensitivity analysis; association remained positive and significant, data NR), physical activity, family history of diabetes, smoking, alcohol intake; - Other: postmenopausal status and menopausal hormone use, oral contraceptive use (NHS-II), modified dietary diabetes risk reduction score; Limitations:; - Did not account for key confounders: socioeconomic position; - No evidence whether the result was biased due to missing data; - No preregistered data analysis plan; Funding:; NIH
Romaguera, 2013 ^25^; PCS, EPIC-InterAct, 5 European countries (France, UK, The Netherlands, Germany, and Denmark); Analytic N=26,328 (subcohort = 15,374); Study objective: To evaluate the association of consumption of sweet beverages (juices and nectars, sugar-sweetened soft drinks and artificially sweetened soft drinks) with T2D incidence in European adults.; Participant characteristics at baseline: adults; - Age (mean and/or range): ~52 (9)y; - Female: 62%; - Race and/or ethnicity: NR; - Socioeconomic position: 21% university education; - Anthropometry: BMI ~26 (4) kg/m^2^; - Physical activity: 20% highest activity level (out of 4 levels); - Family history of diabetes: ~19% (NR in Italy, Spain, Germany, and UK); - Smoking: 26% current; - Alcohol intake: ~2 g/d; - TEI: ~2220 (645) kcal/d; - Beverage intake at baseline: 8% ≥1 glass/d of soft drinks, 24% >1-6 glasses/wk; Excluded from study or analysis: baseline diabetes; missing data; lowest and highest 1% for ratio of total energy intake to energy requirement; Italy, Spain, and Umeå (Sweden) where information on type of soft drink consumption was not collected | Exposure: Sugar-sweetened soft drinks; - Serving Size: 336 g (12oz) in continuous analyses; 1 glass svg = 250 g (~8.8oz) in categorical analyses; Comparator: continuous intake (per 336 g svg); categorical intake (<1 glass/mo, 1-4 glasses/mo, >1-6 glasses/wk, ≥1 glass/d); Assessment methods and timing:; - FFQ or dietary questionnaire (country-specific) assessing usual intake during previous year.; - Baseline; Outcome assessment methods and timing:; - Combination of self-report, linkage to registries, hospital/mortality data; - ~16y | [underlined: T2D by baseline intake], HR (95% CI); By baseline sugar-sweetened soft drink intake; <1 glass/mo: REF; 1-4 glasses/mo: 1.19 (0.91, 1.56); >1-6 glasses/wk: 1.07 (0.94, 1.21); ≥1 glass/d: 1.29 (1.02, 1.63); P-trend=0.013; Per svg (336 g): 1.18 (1.06, 1.32); Subgroup analyses:; <55y: 1.20 (0.94, 1.52); ≥55y: 1.37 (1.07, 1.76); P-interaction=0.75; Men: 1.19 (1.03, 1.39); Women: 1.29 (1.10, 1.51); P-interaction=0.063; BMI <25 kg/m^2^: 1.30 (1.03, 1.66); BMI 25-29.9 kg/m^2^: 1.17 (0.96, 1.42); BMI ≥30 kg/m^2^: 1.28 (1.02, 1.61); P-interaction=0.22; Low physical activity: 1.25 (1.04, 1.49); High physical activity: 1.24 (1.07, 1.43); P-interaction=0.73 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, socioeconomic position (educational level), anthropometry, physical activity, family history of diabetes, smoking, alcohol intake; - Other: other sweet beverages; Limitations:; - Did not account for key confounders: race and/or ethnicity; - Exposure only assessed at baseline; - No evidence whether the result was biased due to missing data; - No preregistered data analysis plan; Funding:; EU FP6 Programme
Rose, 2023 ^39^; NCC, NHS (Nurses’ Health Study), U.S.; Analytic N=2,814; Study objective: To elucidate potential dietary determinants of T2D risk by defining a model that describes habitual beverage consumption profiles in relation to identified networks of circulating plasma biomarkers.; Participant characteristics at baseline: women; - Age (mean and/or range): 56 (7)y; 30-55y; - Female: 100%; - Race and/or ethnicity: Primarily Caucasian; - Socioeconomic position: All nurses; - Anthropometry: BMI 28 (6) kg/m^2^; - Physical activity: ~8 MET hr/wk; - Family history of diabetes: NR; - Smoking: 12% current; 41% former; 48% never; - Alcohol intake: 8% beer; 19% liquor; 9% red wine; 21% white wine; - TEI: ~1800 (450) kcal/d; - Beverage intake at baseline: Cola: 4.2 (3.8) svg/wk; Caffeine-free cola: 3.0 (2.5) svg/wk; SSB: 3.1 (3.0) svg/wk; Excluded from study or analysis: baseline diabetes; cancer or cardiovascular disease; missing data | Exposure: SSB factor (representing higher intake of caffeinated and caffeine-free cola and other sugar-containing carbonated drinks relative to other beverage types) identified from EFA; - Serving Size: NR; Comparator: dichotomous intake (low vs high factor score group); Assessment methods and timing:; - FFQ assessing usual intake during previous year.; - 1984, 1986, 1990 (cumulative average intake); Outcome assessment methods and timing:; - Self-reported via biennial questionnaire; verified with supplementary questionnaire specific to T2D | [underlined: T2D by cumulative average intake], OR (95% CI); Low factor score: REF; High factor score: 1.16 (0.88, 1.52); P=0.417 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, anthropometry, physical activity, alcohol factor; - Other: other beverage factors (fruit juice, SSB/LNCSB, caffeine-free), fasting status at blood draw, case-control status, menopausal status, postmenopausal hormone use, aspirin and multivitamin use, modified AHEI score; Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position, family history of diabetes, smoking; - Exposure subject to measurement error; - No evidence whether the result was biased due to missing data; - No preregistered data analysis plan; Funding:; NIH
Sakurai, 2014 ^40^; PCS, Japan; Analytic N=2,037; Study objective: To investigate the association between SSB and diet soda consumption and the incidence of T2D in Japanese men.; Participant characteristics at baseline: lean middle-aged Japanese men; - Age (mean and/or range): 46.2y; 35-55y; - Female: 0%; - Race and/or ethnicity: All Japanese; - Socioeconomic position: All employed at factory; - Anthropometry: BMI 23.4 kg/m^2^; - Physical activity: 28% habitual exercise; - Family history of diabetes: 13%; - Smoking: 53% current; 15% former; 32% never; - Alcohol intake: 15% never, 11% occasional, 32% <20g/d, 42% ≥20g/d; - TEI: 1998-2627 kcal/d; - Beverage intake at baseline: 12% consumed SSB ≥1 svg/d; median daily intake (range): 0.2 (0.0-9.6) svg; Excluded from study or analysis: baseline diabetes or FPG ≥126 mg/dL or HbA1C ≥6.5%; energy intake <500 or >5000 kcal/d; missing data on SSB; loss to follow-up | Exposure: SSB (“regular soft drinks, sugar-sweetened soda, and sports drinks, excluding 100% fruit juice and vegetable juice”); - Serving Size: 237mL or 8oz; Comparator: categorical intake (rare/never, more often than rare/never but <1 svg/wk, ≥1 svg/wk but <1 svg/d, ≥1 svg/d); Assessment methods and timing:; - Validated diet history questionnaire on intake during previous month; - Baseline; Outcome assessment methods and timing:; - Biomarkers (FPG ≥126 mg/dL and/or HbA1C ≥6.5%); - 5.5 (1.8)y (annually) | [underlined: T2D by baseline intake], HR (95% CI); Rare/never: REF; >Rare/never but <1 svg/wk: 0.97 (0.57, 1.64); ≥1 svg/wk to <1 svg/d: 1.11 (0.74, 1.66); ≥1 svg/d: 1.34 (0.72, 2.36); P-trend=0.424 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity (Japanese), anthropometry, physical activity, family history of diabetes, smoking, alcohol intake; - Other: hypertension dyslipidemia, diet treatment for chronic disease, total fiber intake, other beverage consumption (diet soda, fruit juice, vegetable juice, coffee); Limitations:; - Did not account for key confounders: socioeconomic position; - Exposure only assessed at baseline; - No evidence whether the result was biased due to missing data; - No preregistered data analysis plan; Funding:; Ministry of Health, Labor, and Welfare, Health and Labor Sciences; Ministry of Education, Culture, Sports, Science and Technology of Japan for Scientific Research; Japan Arteriosclerosis Prevention Fund
Schulze, 2004 ^41^; PCS, NHS-II (Nurses’ Health Study II), U.S.; Analytic N=91,249; Study objective: To examine the association between consumption of SSB and weight change and risk of T2D in women.; Participant characteristics at baseline: women; - Age (mean and/or range): ~36 (4.7)y; 24-44y; - Female: 100%; - Race and/or ethnicity: Primarily European ancestry; - Socioeconomic position: All nurses; - Anthropometry: BMI ~24.4 kg/m^2^; - Physical activity: ~19 METs/wk; - Family history of diabetes: ~16% in a first-degree relative; - Smoking: 12% current; - Alcohol intake: ~3 g/d; - TEI: ~1800 kcal/d; - Beverage intake at baseline: NR; Excluded from study or analysis: baseline diabetes; cancer or cardiovascular disease; missing data; implausible total energy intake (<500 or >3500 kcal/d) | Exposure: Sugar-sweetened soft drinks (sugar-sweetened cola and fruit punch); sugar-sweetened cola included “Coke, Pepsi, or other cola with sugar”, “caffeine-free Coke, Pepsi, or other cola with sugar”, and “other carbonated beverages with sugar”; - Serving Size: NR; Comparator: categorical intake (<1/mo, 1-4/mo, 2-6/wk, ≥1/d); Assessment methods and timing:; - FFQ assessing usual intake during previous year.; - 1991, 1995; Outcome assessment methods and timing:; - Self-reported via biennial questionnaire; verified with supplementary questionnaire specific to T2D; - 8y | [underlined: T2D by average intake], RR (95% CI); All sugar-sweetened soft drinks; <1/mo (REF); 1-4/mo: 1.06 (0.87, 1.28); 2-6/wk: 1.49 (1.16, 1.91); ≥1/d: 1.83 (1.42, 2.36); P-trend<0.001; When further controlling for BMI; <1/mo (REF); ≥1/d: 1.39 (1.07, 1.76); P-trend=0.01; When further controlling for TEI; <1/mo (REF); ≥1/d: 1.32 (1.01, 1.73); P-trend=0.04; Also provided results for sugar-sweetened soft drinks stratified by: Obesity status, physical activity level, family history of diabetes, cereal fiber intake, trans-fat intake, and ratio of polyunsaturated to saturated fat (no stratifications showed significant interactions); Sugar-sweetened cola; <1/mo (ref); 1-4/mo: 0.99 (0.80, 1.23); 2-6/wk: 1.56 (1.21, 2.02); ≥1/d: 1.87 (1.43, 2.45); P-trend<0.001; Fruit punch; <1/mo (REF); 1-4/mo: 0.90 (0.68, 1.18); 2-6/wk: 1.15 (0.79, 1.66); ≥1/d: 2.00 (1.33, 3.03); P-trend=0.001 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, anthropometry, physical activity, family history of diabetes, smoking, alcohol intake; - Other: postmenopausal hormone use, oral contraceptive use, intake of cereal fiber, magnesium, trans-fat, ratio of polyunsaturated to saturated fat, and other sugar-sweetened beverage consumption (other than the main exposure, depending on model); Results were similar when adjusting for caffeine, red meat, french fries, processed meat, sweets, snacks, vegetables, and fruit; Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position; - No evidence whether the result was biased due to missing data; - No preregistered data analysis plan; Funding:; NIH; European Association for the Study of Diabetes/American Diabetes Association; German Academic Exchange Service (DAAD)
Srour, 2020 ^42^; PCS, French NutriNet-Santé cohort, France; Analytic N=104,707; Study objective: To assess the associations between consumption of ultra-processed foods and T2D; Participant characteristics at baseline: French adults; - Age (mean and/or range): 42.7 (14.5)y; ≥18y; - Female: 79%; - Race and/or ethnicity: NR; - Socioeconomic position: 59% with education ≥2y after high school; - Anthropometry: 20% with overweight, 8% with obesity; - Physical activity: 28% high, 37% moderate, 21% low; - Family history of diabetes: NR; - Smoking: 17% current; 33% former; 50% never; - Alcohol intake: 3.91 (5.53) g/1000 kcal/d; - TEI: 1847.14 (450.86) kcal/d without alcohol; - Beverage intake at baseline: Sugary drinks, 24.94 (53.64) g/1000 kcal/d; Excluded from study or analysis: baseline diabetes; <18y; missing or invalid dietary data; energy underreporters | Exposure: Ultra-processed beverages, including sugary drinks (e.g., regular sodas, sugary fruit-based beverages, industrial chocolate powder beverages, energy drinks, flavoured waters) and artificially sweetened beverages (e.g., diet sodas, artificially sweetened ice teas); - Serving Size: NR; Comparator: continuous intake (% consumed); Assessment methods and timing:; - Three nonconsecutive 24hr diet records every 6mo; - Baseline (average of first 2y); Outcome assessment methods and timing:; - Self-report based on doctor’s diagnosis or diabetic medication; confirmed with national health insurance database or biomarkers (FBG >1.26 g/L); - Median 6.0y (IQR: 2.8-8.4y) | [underlined: T2D by baseline intake], HR (95% CI); By % consumed (in absolute increments of 10%): 1.13 (1.07, 1.19), P<0.0001 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, socioeconomic position (educational level), anthropometry, physical activity, family history of diabetes, smoking, alcohol intake; - Other: number of 24h dietary records, diet quality index, consumption amount of ultra-processed beverages; Limitations:; - Did not account for key confounders: race and/or ethnicity; - Exposure subject to measurement error (combined SSB and LNCSB) and only assessed at baseline; - No evidence whether the result was biased due to missing data; - No preregistered data analysis plan; Funding:; Ministère de la Santé; Santé Publique France; Institut National de la Santé et de la Recherche Médicale (INSERM); Institut National de la Recherche Agronomique (INRA); Conservatoire National des Arts et Métiers (CNAM); Université Paris 13
Stern, 2019 ^43^; PCS, Mexican Teachers’ Cohort, Mexico; Analytic N=72,667; Study objective: To estimate the association between sugar-sweetened soda consumption and incident diabetes; Participant characteristics at baseline: Mexican women; - Age (mean and/or range): 42.1 (7.2)y; ≥25y; - Female: 100%; - Race and/or ethnicity: All Hispanic; - Socioeconomic position: Median of highest tertile: 6 household assets (IQR: 6-7), including household access to car, telephone, cell phone, microwave, vacuum, computer, and internet; All are public school teachers; - Anthropometry: BMI 27.2 (4.5) kg/m^2^; 38% with overweight, 21% with obesity; - Physical activity: Median of highest tertile: 54.50 MET hr/wk (IQR 41.5-125.5); - Family history of diabetes: 47%; - Smoking: 9% current; 12% former; 76% never; 3% missing; - Alcohol intake: NR; - TEI: NR; - Beverage intake at baseline: Median 1.17 svg/d (IQR: 0.47-4.00); Excluded from study or analysis: baseline diabetes; cancer or heart disease; missing data; energy intake <500 or >3500 kcal/d | Exposure: Sugar-sweetened soda (cola-flavored soda and flavored soda); - Serving Size: 355 mL; Comparator: continuous intake (svg/d) categorical intake (quintiles; ≤1, >1-4, ≥5 svg/wk); Quintiles; Median (IQR):; - Quintile 1 (n=10,680): 0.23 (0.00-0.23); - Quintile 2 (n=13,912): 0.47 (0.47-0.47); - Quintile 3 (n=18,478): 1.17 (0.82-1.17); - Quintile 4 (n=11,404): 3.00 (2.00-3.23); - Quintile 5 (n=18,193): 6.00 (5.50-8.00); Pre-specified categories; Median (IQR):; - Low, ≤1 svg/wk (n=30,109): 0.47 (0.23-0.58); - Moderate, >1 to 2-4 svg/wk (n=29,543): 2.00 (1.17-3.23); - High, ≥5 svg/wk (n=13,015): 7.23 (6.00-10.00); Assessment methods and timing:; - FFQ assessing usual intake during previous year.; - Baseline; Outcome assessment methods and timing:; - Self-report of medical diagnosis of diabetes, use of medical treatment, or date of diabetes diagnosis; validated in subsample using supplementary questionnaire; - Median 2.16y (IQR: 0.75-4.50y) | [underlined: T2D by baseline intake], HR (95% CI); Quintile 1: REF; Quintile 5: 1.14 (1.01, 1.28); P-trend=0.028; ≤1 svg/wk: REF; >1 to 2-4 svg/wk: 1.07 (0.99, 1.16); ≥5 svg/wk: 1.13 (1.02, 1.25); P-trend=0.026; Per 1 svg/d : 1.13 (1.04, 1.23); Nonlinear relation per 1 svg/d using restricted cubic splines (unadjusted for BMI): Data NR (figure only), P=0.0491 | Model adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position (number of assets as measure of SES), anthropometry, physical activity, family history of diabetes, smoking; - Other: region of residence in Mexico (North, Center, Mexico City/Metropolitan area, South); food and beverage groups (fruit, vegetables, red meat, processed meat, whole grains, juice, and diet soda); Limitations:; - Did not account for key confounders: alcohol intake; - Exposure only assessed at baseline; - High attrition rate/missing data; - No preregistered data analysis plan; Funding:; AstraZeneca; Bloomberg Philanthropies; American Institute for Cancer Research; Consejo Nacional de Ciencia y Tecnología
Teshima, 2015 ^45^; PCS, Mihama Diabetes Prevention Study, Japan; Analytic N=93; Study objective: To evaluate the effects of SSB intake on the development of T2D in subjects with impaired glucose tolerance; Participant characteristics at baseline: participants with IGT; - Age (mean and/or range): ~55y; 40-69y; - Female: 68%; - Race and/or ethnicity: All Asian; - Socioeconomic position: NR; - Anthropometry: BMI 24 (3) kg/m^2^; - Physical activity: NR; - Family history of diabetes: NR; - Smoking: NR; - Alcohol intake: NR; - TEI: NR; - Beverage intake at baseline: NR; Excluded from study or analysis: baseline diabetes; normal glucose tolerance; <40 or >69y; severe hepatic or renal disease; history of gastrectomy | Exposure: SSB (including canned coffee, carbonated drinks, and juices); no differentiation between fructose, glucose, or sucrose as the source of sweetness; - Serving Size: NR; Comparator: dichotomous intake (everyday/occasional intake vs no intake); Assessment methods and timing:; - 19-item questionnaire; - Baseline; Outcome assessment methods and timing:; - Annual OGTT; - 3.6 (0.2)y | [underlined: T2D by baseline intake], OR (95% CI); No intake: REF; Everyday/occasional intake: 1.03 (0.331, 3.187) | Model adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity; - Other: duration of observation; Limitations:; - Did not account for key confounders: socioeconomic position, anthropometry, physical activity, family history of diabetes, smoking, alcohol intake; - Exposure subject to measurement error and analyses based on exposure collected only at baseline; - No evidence whether the result was biased due to missing data; - No preregistered data analysis plan; Funding:; None declared
Torres-Ibarra, 2020 ^46^; PCS, Health Workers Cohort Study, Mexico; Analytic N=1,445; Study objective: To estimate the risk of T2D due to soft drinks consumption in a cohort of Mexicans.; Participant characteristics at baseline: Mexican adults; - Age (mean and/or range): 44.3 (12.5)y; ≥19y; - Female: 76%; - Race and/or ethnicity: All Hispanic; - Socioeconomic position: 49% ≥college; 23% high school, 26% middle school or less, 2% missing; All employed at health and academic institutions; - Anthropometry: BMI 26.2 (4.1) kg/m^2^; 17% obesity; - Physical activity: 38% active (≥150 min/wk); 1.5 hr/wk of leisure-time physical activity; - Family history of diabetes: 53%; - Smoking: 17% current; 24% former; 55% never; 4% missing; - Alcohol intake: 33% drink >2.4 g/d; - TEI: ~2150 kcal/d; - Beverage intake at baseline: Median 0.2 svg/d (IQR: 0.10-0.57); 22% consumed ≥5 svg/wk; Excluded from study or analysis: baseline diabetes; <19y; missing data; energy intake <500 or >6400 kcal/d; heart disease or cancer (except skin or melanoma) at baseline; pregnant | Exposure: Soft drinks (cola soft drinks and flavored carbonated soft drinks); - Serving Size: 355 mL; Comparator: categorical intake (<1 time/wk, 1-4 times/wk, ≥5 times/wk); - <1 svg/wk (n=361); - 1-4 svg/wk (n=770); - ≥5 svg/wk (n=314); Assessment methods and timing:; - FFQ assessing usual intake during previous year.; - Baseline; Outcome assessment methods and timing:; - Self-report of physician-diagnosed T2D, fasting glucose >126 mg/dl, or hypoglycemic medication at any examination; - Median 6.7y (IQR: 6.2-7.1y) | [underlined: T2D by baseline intake], HR (95% CI); P-trend=0.040 for multivariate adjusted model; Further adjusted for baseline BMI; <1 svg/wk: REF; 1-4 svg/wk: 1.0 (0.6, 1.7); ≥5 svg/wk: 1.5 (0.8, 2.8); P-trend=0.094; Further adjusted for abdominal obesity; <1 svg/wk: REF; 1-4 svg/wk: 1.1 (0.6, 1.9); ≥5 svg/wk: 1.6 (0.8, 3.0); P-trend=0.083; Stratified by family history of diabetes:; P-interaction=0.4285; No family history of diabetes; <1 svg/wk (n=147): REF; 1-4 svg/wk (n=303): 0.67 (0.25, 1.79); ≥5 svg/wk (n=132): 0.66 (0.20, 2.16); P-trend=0.674; Family history of diabetes; <1 svg/wk (n=189): REF; 1-4 svg/wk (n=402): 1.49 (0.73, 3.07); ≥5 svg/wk (n=166): 2.3 (1.04, 5.17); P-trend=0.037; Data also provided for complete case analysis (N=600), unadjusted for baseline anthropometry | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position (levels of education), anthropometry, physical activity, family history of diabetes, smoking, alcohol intake; - Other: hypertension (separate model not including BMI or abdominal obesity); Limitations:; - Analyses based on exposure collected only at baseline; - Unclear how subsample was selected; - No preregistered data analysis plan; Funding:; Consejo Nacional de Ciencia y Tecnología; Bloomberg Philanthropies
Viana Dias, 2023 ^47^; PCS, CUME (Cohort of Universities of Minas Gerais), Brazil; Analytic N=2,480; Study objective: To evaluate the association between the energy consumption of SSB adjusted for daily energy intake and the incidence of T2D; Participant characteristics at baseline: Brazilian adults; - Age (mean and/or range): 27% ≤30y, 61% 31-49y, 12% ≥50y; - Female: 66%; - Race and/or ethnicity: NR; - Socioeconomic position: All graduated from Brazilian public universities; 54% live with partner; - Anthropometry: 58% with overweight; - Physical activity: 68% scheduled physical exercise; - Family history of diabetes: NR; - Smoking: NR; - Alcohol intake: NR; - TEI: 2239 kcal/d; - Beverage intake at baseline: Median 47.7 kcal/d (~118 mL/d of soft drink, ~100 mL/d of fruit juice box); Excluded from study or analysis: baseline diabetes; energy intake <600 or >6000 kcal/d; pregnant; missing data on physical activity; foreigner or residing outside Brazil | Exposure: SSB, including sugar-sweetened soft drinks and industrialized sugar-sweetened fruit juice (canned/box/powder); - Serving Size: NR; Comparator: dichotomous intake (based on median: ≤47 vs >47 kcal/d); Assessment methods and timing:; - FFQ assessing usual intake during previous year.; - Baseline; Outcome assessment methods and timing:; - Self-report; blood glucose values were validated with a sample of participants; - 2-4y | [underlined: T2D by baseline intake], OR (95% CI); SSB ≤47.7 kcal/d: REF; SSB >47.7 kcal/d: 1.63 (1.00, 2.66); P=0.049 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, anthropometry, physical activity; - Other: marital status; Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position, family history of diabetes, smoking, alcohol intake; - Analyses based on exposure collected only at baseline; - No evidence whether the result was biased due to missing data; - No preregistered data analysis plan; Funding:; None declared
von Ruesten, 2013 ^48^; PCS, EPIC-Potsdam, Germany; Analytic N=23,531; Study objective: To give a comprehensive overview on health-related foods in relation to major chronic diseases based on 8 years of follow-up; Participant characteristics at baseline: adults; - Age (mean and/or range): 35-65y; - Female: 61%; - Race and/or ethnicity: NR; - Socioeconomic position: NR; - Anthropometry: NR; - Physical activity: NR; - Family history of diabetes: NR; - Smoking: NR; - Alcohol intake: NR; - TEI: NR; - Beverage intake at baseline: median ~3.5 g/d of high-energy soft drinks; Excluded from study or analysis: baseline diabetes; CVD or cancer; missing data; energy intake >800 or >6000 kcal/d | Exposure: High-energy soft drinks (cola, lemonade, non-alcoholic beer/malt beer); - Serving Size: 200 g; Comparator: continuous intake (per 1 svg/d); Assessment methods and timing:; - FFQ assessing usual intake during previous year.; - Baseline; Outcome assessment methods and timing:; - Self-report or registries; medically verified with physician inquiry; - 8y | [underlined: T2D by baseline intake], HR (95% CI); Fully-adjusted model: 1.04 (0.96, 1.13); Further adjusted for other food groups: 1.04 (0.95, 1.15) | Model adjustments:; - TEI: yes; - Key confounders: sex, age, socioeconomic position (education), anthropometry, physical activity, smoking, alcohol intake; - Other: prevalent hypertension at baseline, history of high blood lipid levels at baseline, vitamin supplementation, nonconsumption of the respective food group, 45 food groups; Limitations:; - Did not account for key confounders: race and/or ethnicity, family history of diabetes; - Exposure only assessed at baseline; - No evidence whether the result was biased due to missing data; - No preregistered data analysis plan; Funding:; Federal Ministry of Science (Germany); European Community; German Cancer Aid

a Abbreviations: ADA: American Diabetes Association; ASB: artificial sweetened beverage(s); BMI: body mass index; CI: confidence interval; CVD: cardiovascular disease; d: day(s); dL: deciliter; EFA: exploratory factor analysis; EPIC: European Prospective Investigation into Cancer and Nutrition; FFQ: food frequency questionnaire; g: gram(s); HbA1c: hemoglobin A1C; hr: hour; HR: hazard ratio; IAUC: incremental area under the curve; IGT: impaired glucose tolerance; kcal: kilocalorie(s); kg: kilogram(s); L: liter(s); LNCSB: low- and no-calorie sweetened beverage(s); m: meter(s); mg: milligram(s); min: minute(s); mL: milliliter(s); N/A: not applicable; NCC: nested case control study; NIDDK: National Institute of Diabetes and Digestive and Kidney Diseases; NIH: National Institutes of Health; nmol: nanomole; NR: not reported; NS: not significant; OGTT: oral glucose tolerance test; OR: odds ratio; oz: ounce(s); PCS: prospective cohort study; REF: reference group; RR: risk ratio; SD: standard deviation; SE: standard error; SSB: sugar-sweetened beverage(s); svg: serving(s); T2D: type 2 diabetes; TEI: total energy intake; μmol: micromole(s); wk: week(s); y: year(s)

Table 12 Risk of bias for randomized controlled trials examining sugar-sweetened beverage consumption in adults and older adults and risk of type 2 diabetes^a^

Article | Randomization | Deviations from intended interventions (per-protocol) | Missing outcome data | Outcome measurement | Selection of reported result | Overall risk of bias
Campos, 2015^8^ | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Ebbeling, 2020^14^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Engel, 2018^15^ | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Hernandez-Cordero, 2014^21^ | LOW | LOW | LOW | LOW | LOW | LOW
Kendig, 2023^27^ | SOME CONCERNS | HIGH | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Tate, 2012^44^ | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS

a Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898. doi: 10.1136/bmj.l4898 31462531 )

Table 13 Risk of bias for observational studies examining sugar-sweetened beverage consumption in adults and older adults and risk of type 2 diabetes^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of reported result | Overall risk of bias
Bazzano, 2008^6^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Bhupathiraju, 2013^7^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Canhada, 2023^9^ | HIGH | HIGH | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Chen, 2023^10^ | LOW* | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Cho, 2023^11^ | HIGH | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
de Koning, 2011^12^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Drouin-Chartier, 2019^13^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Ericson, 2018^16^ | HIGH | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Eshak, 2013^17^ | LOW* | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Fagherazzi, 2013^18^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Gardener, 2018^19^ | HIGH | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Greenberg, 2005^20^ | SOME CONCERNS | HIGH | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Hirahatake, 2019^22^ | LOW* | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Huang, 2017^23^ | LOW* | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Imamura, 2019^24^ | SOME CONCERNS | HIGH | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Jahromi, 2023^26^ | HIGH | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
McNaughton, 2008^28^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Montonen, 2007^29^ | HIGH | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Nettleton, 2009^30^ | HIGH | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
O’Connor, 2016^31^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Odegaard, 2010^32^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Olsson, 2021^33^ | HIGH | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Palmer, 2008^34^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Pan, 2012^35^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Paynter, 2006^36^ | LOW* | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Ramne, 2020^37^ | HIGH | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Rhee, 2015^38^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Romaguera, 2013^25^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Rose, 2023^39^ | HIGH | HIGH | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Sakurai, 2014^40^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Schulze, 2004^41^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Srour, 2020^42^ | SOME CONCERNS | HIGH | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Stern, 2019^43^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Teshima, 2015^45^ | HIGH | HIGH | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Torres-Ibarra, 2020^46^ | LOW* | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Viana Dias, 2023^47^ | HIGH | HIGH | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
von Ruesten, 2013^48^ | HIGH | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH

a Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the “Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)” tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24). doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.