# Results

## Literature search and screening results

The literature search was conducted to identify all potentially relevant articles for 2 systematic reviews assessing beverages and risk of type 2 diabetes: low- and no-calorie sweetened beverages^†^ and sugar-sweetened beverages. The literature search (Appendix 2) yielded 16,910 search results after the removal of duplicates (see Figure 2). Dual-screening resulted in the exclusion of 14,523 titles, 2,054 abstracts, and 281 full-text articles. Reasons for full-text exclusion are in Appendix 3. Five additional articles were identified from the manual search. The body of evidence included 48 articles on sugar-sweetened beverages:

- Infants and young children: 0 articles
- Children and adolescents: 5 articles^1–5^
- Adults and older adults: 43 articles^6–48^

† Giovannucci E, Taylor CA, Deierlein AL, . Low- and No-Calorie Sweetened Beverages and Risk of Type 2 Diabetes: A Systematic Review. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review; 2025. 10.52570/NESR.DGAC2025.SR15

Figure 2 Literature search and screen flowchart

The literature search in PubMed, Embase, Cochrane, and CINAHL, retrieved 16,910 records after removing duplicates. Five were found through other manual search methods. 14,523 titles, 2054 abstracts, and 281 full-texts were excluded. 57 articles were included across the two systematic reviews examining beverage consumption and risk of type 2 diabetes. 48 articles were included in the systematic review on sugar-sweetened beverages.

## Infants and young children

### Description of the evidence

No articles examined the relationship between sugar-sweetened beverage consumption in infants and young children up to age 24 months and risk of type 2 diabetes.

### Conclusion statement and grade

The Committee was not able to develop a conclusion statement to answer the question “What is the relationship between sugar-sweetened beverage consumption and risk of type 2 diabetes?” based on the lack of evidence in infants and young children up to age 24 months (Table 5).

Table 5 Conclusion statement and grade for sugar-sweetened beverage consumption in infants and young children and risk of type 2 diabetes

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between sugar-sweetened beverage consumption by infants and young children up to age 24 months and risk of type 2 diabetes because there is no evidence available.
Grade | Grade Not Assignable
Body of Evidence | 0 articles
Rationale | There were no eligible articles examining sugar-sweetened beverage consumption by infants and young children and risk of type 2 diabetes.

## Children and adolescents

### Description of the evidence

Five articles examined the relationship between sugar-sweetened beverage consumption in children and adolescents and risk of type 2 diabetes (Table 8).^1–5^ All included articles were from prospective cohort studies.

#### Population

Studies were conducted in populations from the following countries and cohorts:

- Australia: 1 article from the Western Australian Pregnancy Cohort (Raine)^1^
- Germany: 2 articles from the DOrtmund Nutritional and Anthropometric Longitudinally Designed (DONALD) Study^4,5^
- Iran: 1 article from the Tehran Lipid and Glucose Study^2^
- United States: 1 article from the Exploring Perinatal Outcomes among CHildren (EPOCH) Study^3^

The articles had a mean baseline age ranging from approximately 9.5 to 14 years. Sample sizes ranged from N=226 to N=1124, with 49 to 68% female enrollment. Four articles did not report data on race and/or ethnicity^1,2,4,5^; the EPOCH study comprised of 48% non-Hispanic White, 8% non-Hispanic Black, 5% non-Hispanic Other, and 39% Hispanic participants.^3^ Four articles reported data on parental education levels^1,2,4,5^; the EPOCH study^3^ did not report data on socioeconomic position. All studies included participants across BMI weight status categories.

#### Intervention/exposure and comparator

The intervention or exposure for this systematic review question was sugar-sweetened beverages. Eligible comparators were consumption of different amounts of sugar-sweetened beverages (including no consumption and versions diluted with water), water, or low- and no-calorie sweetened beverages. Studies that compared sugar-sweetened beverages to low- and no-calorie sweetened beverages were included in this review and not the review on low- and no-calorie sweetened beverages.^*^ All included articles examined different amounts of sugar-sweetened beverages as a categorical variable (i.e., tertiles, quartiles). Most studies examined sugar-sweetened beverage intake at baseline online; only Ambrosini et al^1^ measured intake at multiple time points. Three studies measured sugar-sweetened beverage intake using a food frequency questionnaire.^1–3^ In the DONALD study, sugar-sweetened beverage intake was measured using two 3-day weighed food records.^4,5^ Mirmiran et al^2^ examined sugar-sweetened carbonated soft drinks but did not differentiate drinks containing artificial non-caloric sweeteners from drinks containing caloric sugar; the study also examined “combined fruit juice drinks”, which combined sugar-sweetened synthetic juice drinks and 100% fruit juice drinks. Cohen et al^3^ included sweetened tea or coffee in their measure of sugar-sweetened beverages.

* Giovannucci E, Taylor CA, Deierlein AL, . Low- and No-Calorie Sweetened Beverages and Risk of Type 2 Diabetes: A Systematic Review. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review; 2025. 10.52570/NESR.DGAC2025.SR15

#### Outcome

The following outcomes were reported:

- Fasting blood glucose: 3 articles^1–3^
- Fasting insulin: 3 articles^1,3,4^
- Glucose tolerance/insulin resistance: 4 articles^1,3–5^ from 3 studies

None of the included articles examined hemoglobin A1C, prediabetes, or type 2 diabetes. All studies collected fasting blood samples using standard methods. Two studies^1,2^ examined change in outcomes over a 3-year follow-up, Cohen et al^3^ examined change in outcomes over a 6-year follow-up, and both articles^4,5^ from the DONALD study collected fasting blood samples only in adulthood.

### Synthesis of the evidence

Synthesis in children and adolescents focused on fasting blood glucose, fasting insulin, and glucose tolerance/insulin resistance due to a lack of data on hemoglobin A1C, prediabetes, and type 2 diabetes.

#### Fasting blood glucose

Out of 3 articles, all reported no association between sugar-sweetened beverage consumption and fasting blood glucose; all but 1 study^1^ controlled for total energy intake. Two studies found similar changes in fasting glucose between those with the highest categorical intake of sugar-sweetened beverage compared to those with the lowest intake.^1,3^ In Mirmiran et al^2^, children and adolescents in the highest quartile of sugar-sweetened beverage consumption (median intake 142.2 mL/day) had similar odds of incident high fasting plasma glucose (≥100 mg/dL according to American Diabetes Association recommendations) at follow-up approximately 3.6 years later compared to those in the lowest quartile with median sugar-sweetened beverage intake of 9.3 mL/d (OR =1.95, 95% CI=0.73-5.22; p=0.108 for trend).

#### Fasting insulin

Out of 3 articles, all reported no association between sugar-sweetened beverage consumption and fasting insulin; all but 1 study^1^ controlled for total energy intake. All studies found similar changes in fasting insulin, but with varying direction, between the highest and lowest categorical intake of sugar-sweetened beverages.^1,3,4^

#### Glucose tolerance/insulin resistance

Out of 4 articles, all reported no association between sugar-sweetened beverage consumption and glucose tolerance/insulin resistance; all but 1 study^1^ controlled for total energy intake. Two studies found similar changes in homeostatic model assessment for insulin resistance (HOMA-IR), but with varying direction and magnitude, between those with the highest categorical intake of sugar-sweetened beverage compared to those with the lowest intake.^1,3^ In the DONALD study, children and adolescents in the highest tertile of sugar-sweetened beverage intake (32-33 grams per day) had similar mean values for HOMA-IR and homeostasis model assessment of insulin sensitivity (the reciprocal of HOMA-IR) during adulthood.^4,5^

### Conclusion statement and grade

The Committee was not able to develop a conclusion statement to answer the question “What is the relationship between sugar-sweetened beverage consumption and risk of type 2 diabetes?” based on their review of evidence in children and adolescents (Table 6).

Table 6 Conclusion statement and grade for sugar-sweetened beverage consumption in children and adolescents and risk of type 2 diabetes

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between sugar-sweetened beverage consumption by infants and young children up to age 24 months and risk of type 2 diabetes because there is no evidence available.
Grade | Grade Not Assignable
Body of Evidence | 5 articles: all prospective cohort studies
Rationale | - Substantial concerns with directness, particularly with no studies examining the primary outcome of interest; - Some concerns with risk of bias for potential confounding (due to not accounting for key confounders)

The body of evidence underlying the conclusion statement includes 5 articles from prospective cohort studies. All studies examined the relationship between different levels of sugar-sweetened beverage consumption and fasting blood glucose, fasting insulin, and glucose tolerance/insulin resistance. Sugar-sweetened beverage intake was assessed as a categorical measure with 3-day weighed food records or food frequency questionnaire. Most outcome measures were examined continuously. There was no evidence that sugar-sweetened beverage consumption was associated with risk of type 2 diabetes. Studies found that increasing sugar-sweetened beverage intake resulted in similar changes in fasting blood glucose, fasting insulin, and measures of glucose tolerance/insulin resistance (specifically HOMA-IR) in children and adolescents. None of the studies specifically examined the endpoint outcome of incidence of type 2 diabetes.

Most studies had sample sizes between 200 and 600 participants. Studies had numerous risks of bias across domains (Table 9). Several articles were at higher risk of bias due to confounding for not accounting for multiple key confounders (such as race and/or ethnicity, physical activity, and family history of diabetes). Most studies were at higher risk of bias due to exposure misclassification for not accounting for change in sugar-sweetened beverage intake over time. There were also concerns due to missing data and selection of the reported results, as none of the studies had a pre-determined analysis plan. Additionally, there is risk of publication bias because a search of gray literature was not conducted. However, publication bias was not a serious concern for this body of evidence because studies reported mostly nonsignificant findings. There was a lack of data on race and/or ethnicity; only 1 study from the United States reported data on race and/or ethnicity. Furthermore, children under 9 years of age and adolescents over 14 years were under-represented in this body of evidence.

## Adults and older adults

### Description of the evidence

Forty-three articles (34 studies) examined the relationship between sugar-sweetened beverage consumption in adults and older adults and risk of type 2 diabetes. Six articles^8,14,15,21,27,44^ were from randomized controlled trials (RCT) and 37 articles were from 28 observational studies (1 nested case control^39^ and 36 prospective cohort studies^6,7,9–13,16–20,22–26,28–38,40–43,45–48^). Evidence for sugar-sweetened beverage consumption in adults and older adults and risk of type 2 diabetes is summarized in Table 10 (RCT) and Table 11 (observational). Risk of bias assessments for each article are detailed in Table 12 (RCT) and Table 13 (observational).

#### Population

Among trials, mean baseline age ranged from 23 to 42 years. One trial^21^ enrolled only females and another trial^44^ was 84% female; all other trials had even distribution of male and female enrollment. Analytic sample sizes of study groups among the trials ranged from N=27 to N=313.

Among observational studies, mean baseline age ranged from 25 to 69 years. Three studies^19,23,30^ were conducted in participants with a mean age ≥60 years and 1 study^20^ provided data separately for adults ≥60 years. Six studies (9 articles^6,18,23,34,35,38,39,41,43^) enrolled only females and 2 studies^12,40^ enrolled only males. Sample sizes ranged from N=93 to N=198,636. Fourteen articles had analytic sample sizes less than 10,000 participants.^11,19,20,22,26,28–30,37,39,40,45–47^

Multiple articles were from the same cohort study (such as EPIC, the European Prospective Investigation into Cancer and Nutrition) and were included when the article reported unique data. Studies were conducted in populations from the following countries:

- Australia: 1 article from an RCT^27^
- Brazil: 1 article from ELSA-Brasil^9^ and 1 article from Cohort of Universities of Minas Gerais (CUME)^47^
- Denmark: 1 article from an RCT^15^
- Finland: 1 article from the Finnish Mobile Clinic Health Examination^29^
- France: 1 article from EPIC-E3N (Etude Epidémiologique auprès de femmes de la Mutuelle Générale de l’Education Nationale) cohort^18^ and 1 article from the French NutriNet-Santé cohort^42^
- Germany: 1 article from the EPIC-Potsdam study ^48^
- Iran: 1 article from the Tehran Lipid and Glucose Study^26^
- Japan: 1 article from the Japan Public Health Center-based prospective study^17^, 1 article from an unnamed cohort study^40^, and 1 article from the Mihama Diabetes Prevention Study^45^
- Mexico: 1 article from an RCT,^21^ 1 article from the Mexican Teachers’ Cohort,^43^ and 1 article from the Health Workers Cohort Study^46^
- Singapore: 1 article from the Singapore Chinese Health study^32^
- South Korea: 1 article from Korean Genome and Epidemiology Study (KoGES)^11^
- Sweden: 3 articles from the Malmö Diet and Cancer study^16,33,37^
- Switzerland: 1 article from an RCT^8^
- United Kingdom: 1 article from the EPIC-Norfolk cohort^31^ and 1 article from the Whitehall-II cohort^28^
- United States: 1 article from an RCT^14^, 1 article from the Choose Healthy Options Consciously Everyday (CHOICE) trial,^44^ and 16 articles from 10 cohorts^6,7,10,12,13,19,20,22,23,30,35,36,38,39,41^
  ○ The cohorts included: Atherosclerosis Risk in Communities Study (ARIC)^36^; Black Women’s Health Study^34^; Coronary Artery Risk Development in Young Adults Study (CARDIA)^22^; Health Professionals Follow-Up Study (HPFS)^7,10,12,13^; Multi-Ethnic Study of Atherosclerosis (MESA)^30^; NHANES-1 Epidemiologic Follow Up Study (NHEFS)^20^; Northern Manhattan Study^19^; Nurses’ Health Study (NHS)^6,7,10,13,38,39^ and NHS-II^10,13,35,38,41^; Women’s Health Initiative^23^
- Multiple European countries: 2 articles from the EPIC-InterAct study^24,25^

##### Race and/or ethnicity

Among trials, 3 trials did not report data on race and/or ethnicity.^8,15,27^ Of the trials from the United States, 1 trial^14^ consisted of 51% White, 20% Black, 13% Asian, 17% Multiple/Other, and 12% Hispanic participants and another trial^44^ was 40% White, 54% Black, and 6% Other. Among observational studies, 7 studies (13 articles^6,7,10,12,13,23,28,31,35,36,38,39,41^) were in predominantly white/Caucasian populations (>75%). Four studies from the United States had more diverse racial and/or ethnic representation: 100% African American^34^; 50% Black and 50% White^22^; 53% Hispanic, 22% Black, 23% White, 2% Other^19^; 43% White, 23% African American, 21% Hispanic, 12% Chinese^30^. Twelve articles did not report data on race and/or ethnicity.^16,18,20,24–26,29,33,37,42,47,48^

##### Socioeconomic position

Among trials, 3 trials^8,15,27^ did not report data on socioeconomic position. In 2 trials from the U.S., over half of the participants had a bachelor’s degree or higher.^14,44^ Among observational studies, 4 studies (10 articles^6,7,10,12,13,35,38,39,41,47^) enrolled primarily well-educated samples; twenty studies (23 articles^9,11,16–18,20,22–26,28,30–34,36,37,40,42,43,46^) were diverse in terms of participant education and/or income levels and 4 studies^19,29,45,48^ did not report data on socioeconomic position.

##### Health status

Among trials, 4 trials^8,15,21,44^ had inclusion criteria for BMI ≥25 kg/m^2^ and 2 trials^14,27^ included participants across BMI weight status categories. One trial^15^ included participants that were nonsmokers and 3 trials^8,14,27^ did not report data on smoking. No trials reported data on family history of diabetes. Among observational studies, participant mean BMI at baseline ranged from 23 to 28 kg/m^2^. Most articles (25 out of 37) reported a mean BMI ≥25 kg/m^2^. One study did not report baseline anthropometry.^48^ Most articles (29 out of 37) reported current smoking in 9% to 30% of participants; 2 articles^29,40^ had >30% of current smokers, 1 article^16^ included 62% current/former smokers, 1 article^23^ reported current smoking in 4% of female participants, and 4 articles^18,45,47,48^ did not report data on smoking. Participants with family history of diabetes ranged from 7% to 53%; thirteen articles^11,16,19,28,30,32,33,37,39,42,45,47,48^ did not report data on family history of diabetes.

#### Intervention/exposure and comparator

The intervention or exposure for this systematic review question was sugar-sweetened beverages. Eligible comparators were consumption of different amounts of sugar-sweetened beverages (including no consumption and versions diluted with water), water, or low- and no-calorie sweetened beverages. Studies that compared sugar-sweetened beverages to low- and no-calorie sweetened beverages were included in this review and not the review on low- and no-calorie sweetened beverages.^*^

* Giovannucci E, Taylor CA, Deierlein AL, . Low- and No-Calorie Sweetened Beverages and Risk of Type 2 Diabetes: A Systematic Review. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review; 2025. 10.52570/NESR.DGAC2025.SR15

Among trials, all but 1 study^21^ compared sugar-sweetened beverage consumption to low- and no-calorie sweetened beverage consumption. Five trials also compared sugar-sweetened beverage consumption to water consumption.^14,15,21,27,44^ The interventions and comparators in the trials are detailed below:

- Campos et al^8^: a 12-week intervention in which participants drank 2 or more 660-mL servings a day (habitual intake) of carbonated soft drinks and sugar-sweetened tea compared to a group that drank artificially sweetened beverages to replace 2 or more 660-mL servings a day (habitual intake) of sugar-sweetened beverages; both groups were provided with drinks weekly.
- Ebbeling et al^14^: a 52-week intervention in which the intervention group was instructed to drink sugar-sweetened beverages at the same number of servings per day (≥12 fluid ounces) as their usual consumption compared to a group that was instructed to drink artificially-sweetened/diet beverages at the same number of servings per day as their usual consumption of sugar-sweetened beverages and compared to a group that was instructed to drink water (but not artificially- or sugar-sweetened beverages); all groups had beverages delivered to their home.
- Engel et al^15^: a 26-week intervention in which the intervention group drank sucrose-sweetened regular cola compared to a group that drank aspartame-sweetened diet cola and compared to a group that drank still mineral water; all groups consumed 1 liter per day of the beverage.
- Hernandez-Cordero et al^21^: a 9-month (39-week) intervention in which participants with habitually high sugar-sweetened beverage intake (≥250 kilocalories per day) were randomized to 1 of 2 groups: water/education or education only. In the water/education group, participants received 2-3 liters per day of bottled water plus monthly face-to-face nutrition counseling, which targeted strategies to increase water intake, reduce sugar-sweetened beverage intake, and substitute water for sugar-sweetened beverages. In the education only group, participants consumed their habitual sugar-sweetened beverage intake plus monthly face-to-face nutrition counseling.
- Kendig et al^27^: a 12-week intervention in which the intervention group drank commercially-available sugar-sweetened beverages compared to a group that drank diet drinks sweetened with aspartame, acesulfame-K, and sucralose, and compared to the control group who drank water; all groups had beverages delivered to their home and consumed 4.5 liters per week as twelve 375-mL cans.
- Tate et al^44^: a 26-week weight loss intervention in which participants with high habitual sugar-sweetened beverage intake (≥280 kilocalories per day) were assigned to 1 of 3 groups: attention control (maintain sugar-sweetened beverage intake), diet beverages, or water. The “attention control” group participated in monthly group sessions, weigh-ins, and weekly monitoring, and received general weight-loss information; participants in the “attention control” group were not encouraged to change beverage intake and were not provided with beverages. The diet beverage group was encouraged to replace ≥2 servings a day (≥200 kilocalories) of caloric beverages with diet beverages (provided in four 355-500 mL single-servings each day), whereas the water group was encouraged to replace caloric beverages with bottled still and non-sweetened sparking water.

Among observational studies, 18 articles^6,7,9–12,19,20,22–25,31,35,38,42,43,48^ examined continuous beverage intake (e.g., servings per day); whereas, 16 articles^13,16–18,26,28–30,32–34,36,37,40,41,46^ only compared intake across categories (e.g., tertiles, quintiles) and 3 articles^39,45,47^ examined dichotomous intake. Twenty-eight articles examined sugar-sweetened beverage intake using a food frequency questionnaire^6,7,9–13,16,17,19,20,23,26,28,30,32–39,41,43,46–48^; 5 articles^18,22,29,40,45^ used a diet history questionnaire, 1 article^31^ used a 7-day food diary, and 1 article^42^ used three 24-hour diet records. Two articles from the EPIC-InterAct study used either a dietary questionnaire or country-specific food frequency questionnaire to assess usual intake during the previous year.^24,25^ Twenty-six articles examined beverage intake at baseline only^9,11,16,18–20,23–26,28–34,36,37,40,42,43,45–48^ and 11 articles^6,7,10,12,13,17,22,35,38,39,41^ (5 studies) examined change in beverage intake over time.

#### Outcome

The following outcomes were reported:

- Fasting blood glucose: 5 trials^8,14,15,21,44^
- Fasting insulin: 3 trials^8,14,15^
- Glucose tolerance/insulin resistance: 4 trials^8,14,15,27^
- Hemoglobin A1C: 1 trial^21^
- Type 2 diabetes: 37 articles^6,7,9–13,16–20,22–26,28–43,45–48^ from 28 observational studies

Among trials, outcome measures included risk factors for the development of type 2 diabetes (i.e., fasting blood glucose, fasting insulin, measures of glucose tolerance/insulin resistance, and hemoglobin A1C). All trials collected fasted blood samples and/or measured oral glucose tolerance using standard methods at baseline and follow-up. For intervention duration, 1 trial^14^ was 52 weeks, 1 trial^21^ was 9 months (39 weeks), 2 trials^15,44^ were 6 months, and 2 trials^8,27^ were 12 weeks. No included trials examined incidence of impaired fasting blood glucose, prediabetes, or type 2 diabetes.

Among observational studies, 19 of 37 articles used self-report of type 2 diabetes diagnosis, but all verified the accuracy of diagnosis.^6,7,10,12,13,17–19,23,31,32,34–36,38,39,41,43,47^ Nine articles collected fasting blood samples to confirm diagnosis.^9,11,22,26,28,30,40,45,46^ and 4 articles^16,29,33,37^ used national registries. Five articles used a combination of self-report, linkage to registries, and hospital/mortality data.^20,24,25,42,48^ Most studies reported type 2 diabetes incidence using standard criteria or definitions (such as the National Diabetes Data Group, American Diabetes Association, or World Health Organization for biomarkers) and/or treatment with hypoglycemic medication (insulin or oral hypoglycemic agent). Average follow-up duration ranged from 2 to 25 years.

### Synthesis of the evidence

Synthesis in adults and older adults focused on incidence of type 2 diabetes in observational studies, since there were few studies on fasting blood glucose, fasting insulin, glucose tolerance/insulin resistance, and hemoglobin A1C, and no studies on prediabetes. The results for each reported outcome are detailed below:

#### Fasting blood glucose

Out of 5 trials, most reported null effect of sugar-sweetened beverage consumption on fasting blood glucose; 2 trials^8,15^ adjusted for total energy intake. Campos et al^8^ compared habitual intake of sugar-sweetened beverages to replacement with artificially-sweetened beverages, and both groups maintained baseline fasting plasma glucose levels after 12 weeks (mean values ranging from 5.1 to 5.4 mmol/L). In Ebbeling et al^14^, sugar-sweetened beverage intake increased fasting glucose by 1.8±0.8 mg/dL over 12 months, but this increase was similar to water intake and there was no statistically significant difference compared to artificially-sweetened beverage intake. Engel et al^15^ found similar changes in fasting glucose over 6 months between groups that consumed sugar-sweetened beverages, water, or artificially-sweetened non-caloric soft drinks. Hernandez-Cordero et al^21^ found similar changes in fasting glucose at 3, 6, and 9 months between the group that continued habitual intake of sugar-sweetened beverages (education only) and the water/education group. In Tate et al^44^, the group that replaced caloric beverages with water showed significant improvements in fasting glucose of −3.21 mg/dL (95% CI: −3.89, −2.53) compared with the attention control group that continued habitual intake of sugar-sweetened beverages (0.59 mg/dL; 95% CI: 0.35, 0.83); the group that replaced caloric beverages with diet beverages decreased fasting glucose by −1.92 mg/dL (95% CI: −2.38, −1.46), but this was not significantly different from the attention control group.

#### Fasting insulin

Out of 3 trials, all reported null effect of sugar-sweetened beverage consumption on fasting insulin compared to intake of water or low- and no-calorie sweetened beverages; 2 trials^8,15^ adjusted for total energy intake. When comparing sugar-sweetened beverages to low- and no-calorie sweetened beverages, sugar-sweetened beverage intake tended to increase fasting insulin whereas low-and no-calorie sweetened beverage intake tended to decrease fasting insulin; however, these changes were not statistically significant. Two trials found similar changes in fasting insulin when comparing sugar-sweetened beverage intake to water.^14,15^

#### Glucose tolerance/insulin resistance

Out of 4 trials, all reported null effect of sugar-sweetened beverage consumption on glucose tolerance/insulin resistance; 2 trials^8,15^ adjusted for total energy intake. Campos et al^8^ found similar changes in HOMA-IR over 12 weeks between participants who drank carbonated soft drinks and sugar-sweetened tea compared to those who drank artificially-sweetened beverages. Engel et al^15^ found similar changes in measures of insulin sensitivity assessed by a 120-minute oral glucose tolerance test between intake of sucrose-sweetened regular cola, aspartame-sweetened cola, and water. In Ebbeling et al^14^, sugar-sweetened consumption decreased insulin sensitivity by −7.5±6.1 percent after 12 months but this was not significant; there was no significant difference in insulin sensitivity between intake of sugar-sweetened beverages, water, or artificially-sweetened beverages. Kendig et al^27^ found similar changes in a 60-minute oral glucose tolerance test over 12 weeks between participants that drank sugar-sweetened beverages, artificially-sweetened beverages, and water.

#### Hemoglobin A1C

In Hernandez-Cordero et al^21^, those that continued habitual intake of sugar-sweetened beverages (education only) increased HbA1C over 9 months (0.02±0.03) whereas the group that was given water decreased HbA1C (−0.03±0.03); however, this difference was not statistically significant.

#### Type 2 diabetes

Studies evaluating the association between sugar-sweetened beverage intake and incidence of type 2 diabetes reported different effect measures (hazard ratio, risk ratio, and odds ratio). Overall, the effect measures indicated an elevated risk of type 2 diabetes at 2 to 25 years of follow-up. Out of 37 articles, 26 articles (20 observational studies) reported an association between higher amounts of sugar-sweetened beverages consumed and higher risk of type 2 diabetes.^6,7,9–13,16–20,22–26,29,31,32,35,38,41–43,47^ All but 2 studies^9,11^ accounted for anthropometry at baseline, and all but 4 studies^9,20,35,43^ adjusted for total energy intake. Most articles used a food frequency questionnaire to assess sugar-sweetened beverage consumption; 3 articles^18,22,29^ used a diet history questionnaire, 1 article^31^ used a 7-day food diary, and 1 article^42^ used three 24-hour diet records. Most articles examined beverage intake at baseline only; 10 articles^6,7,10,12,13,17,22,35,38,41^ (5 studies) examined change in beverage intake over time.

Eleven articles (10 observational studies) reported no association between sugar-sweetened beverage consumption and incidence of type 2 diabetes.^28,30,33,34,36,37,39,40,45,46,48^ Of these articles, 2 studies^34,46^ reported an association between higher amounts of sugar-sweetened beverages consumed and higher incidence of type 2 diabetes in models that did not account for anthropometry at baseline, but these findings were attenuated when adjusted for BMI. All but 2 studies^37,45^ accounted for anthropometry at baseline, and all but 2 studies^28,45^ adjusted for total energy intake. Most articles used a food frequency questionnaire to assess sugar-sweetened beverage consumption; 2 articles^40,45^ used a diet history questionnaire. Most articles beverage intake at baseline only; 2 articles^34,39^ examined change in beverage intake over time.

### Conclusion statement and grade

The Committee developed a conclusion statement to answer the question “What is the relationship between sugar-sweetened beverage consumption and risk of type 2 diabetes?” based on their review of evidence in adults and older adults (Table 7).

Table 7 Conclusion statement and grade for sugar-sweetened beverage consumption in adults and older adults and risk of type 2 diabetes

Conclusion Statement | Sugar-sweetened beverage consumption by adults and older adults may be associated with higher risk of type 2 diabetes. This conclusion statement is based on evidence graded as moderate.
Grade | Moderate
Body of Evidence | 43 articles: 6 RCT, 1 nested case control, 36 from prospective cohort studies
Consistency | Minimal variation in the direction and significance of findings
Precision | Strengths demonstrated by large sample sizes with adequate number of cases and narrow variance
Risk of bias | Some concerns due to potential for confounding and missing data
Directness | Few concerns with directness across studies
Generalizability | Some concerns with low diversity in reported race and/or ethnicity and socioeconomic position

#### Assessment of the evidence

The body of evidence underlying the conclusion statement includes 6 randomized controlled trials and 37 observational studies. The strength of the evidence was graded based on an assessment of 5 grading elements, as described below. While the literature search was comprehensive, a search of the gray literature was not done, which may increase the possibility of publication bias. However, publication bias was not a serious concern for this body of evidence because several small and large studies were included, and some studies reported null findings.

##### Consistency

The direction of findings was generally consistent. Most observational studies reported an association between higher sugar-sweetened beverage consumption and higher incidence of type 2 diabetes. All trials compared sugar-sweetened beverage consumption to water or low- and no-calorie sweetened beverages. While most trials found null effects, the studies suggested that sugar-sweetened beverage intake could be related to unfavorable changes in fasting blood glucose, fasting insulin, glucose tolerance/insulin resistance, and hemoglobin A1C.

##### Precision

Most trials had concerns with sufficient power (i.e., the study did not report a power calculation or was based on reported power calculations that were not sufficiently powered). Most observational studies demonstrated statistically significant effects that came from a wide range of sample sizes (N=2,019 up to N=198,636) and demonstrated minimal variance (e.g., narrow confidence intervals).

##### Risk of bias

Most trials had some concerns with bias from the randomization process and lacked a data analysis plan in the trial registry. Six out of 37 articles of observational studies accounted for all key confounders. Several observational studies did not account for race and/or ethnicity, socioeconomic position, and/or family history of diabetes. Some articles were at higher risk of exposure mismeasurement for not accounting for change in beverage intake that may occur during follow-up. There were also concerns due to missing data (large study cohorts with high attrition or exclusion) and selection of the reported results, as none of the observational studies had a pre-determined analysis plan.

##### Directness

Most studies were designed to directly examine the relationship between sugar-sweetened beverage consumption and risk of type 2 diabetes. Three trials^8,15,21^ examined cardiometabolic risk factors as the primary outcome, whereas the main objective of the other 3 trials was to examine change in weight. All of the observational studies were designed to directly answer the research question.

##### Generalizability

The review included studies from 16 countries with similar HDI classification as the United States. The body of evidence has applicable interventions/exposures and outcomes relative to the U.S. population, but there were concerns with low diversity in reported race and/or ethnicity and socioeconomic position. A third of the studies (12 out 34) were conducted in the United States, and of these, only 7 were diverse in racial and/or ethnic representation and socioeconomic position. The body of evidence included many participants with overweight or obesity, or other risk factors for cardiometabolic disease.