# Plain language summary

### What is the question?

The question is: What is the relationship between sugar-sweetened beverage consumption and risk of type 2 diabetes? The populations of interest for this question include infants and young children up to age 24 months, children and adolescents, and adults and older adults.

### Why was this question asked?

This systematic review was conducted by the 2025 Dietary Guidelines Advisory Committee as part of the process to develop the Dietary Guidelines for Americans, 2025-2030.

### How was this question answered?

The Committee conducted a systematic review to answer this question with support from the USDA Nutrition Evidence Systematic Review team.

### What is the answer to the question?

#### Infants and young children up to age 24 months

- A conclusion statement cannot be drawn about the relationship between sugar-sweetened beverage consumption by infants and young children up to age 24 months and risk of type 2 diabetes because there is no evidence available.

#### Children and adolescents

- A conclusion statement cannot be drawn about the relationship between sugar-sweetened beverage consumption by children and adolescents and risk of type 2 diabetes because of substantial concerns with directness in the body of evidence.

#### Adults and older adults

- Sugar-sweetened beverage consumption by adults and older adults may be associated with higher risk of type 2 diabetes. This conclusion statement is based on evidence graded as moderate.

### How up-to-date is this systematic review?

Conclusion statements from this review are based on articles published between January 2000 and January 2024.