# Appendix 3 Excluded articles

The following table lists the articles excluded after full-text screening for this systematic review question. At least one reason for exclusion is provided for each article, though this may not reflect all possible reasons. Information about articles excluded after title and abstract screening is available upon request.

Table A 6 Articles excluded after full-text screening

# | Citation | Rationale
1 | Aljamal A, Al-Shawabkeh M, Abu-Zaiton A, et al. Effect of Green Coffee and Orlistat on Obese Individuals. International Journal of Pharmacology. 2022. 18:864-868. doi:10.3923/ijp.2022.864.868 | Intervention/exposure
2 | Alperet DJ, Butler LM, Koh WP, Yuan JM, van Dam RM. Influence of temperate, subtropical, and tropical fruit consumption on risk of type 2 diabetes in an Asian population. Am J Clin Nutr. 2017;105(3):736-745. doi:10.3945/ajcn.116.147090 | Intervention/exposure
3 | Alvarsson M, Hilding A, Ostenson CG. Factors determining normalization of glucose intolerance in middle-aged Swedish men and women: a 8-10-year follow-up. Diabet Med. 2009;26(4):345-353. doi:10.1111/j.1464-5491.2009.02685.x | Intervention/exposure
4 | Angelopoulos TJ, Lowndes J, Rippe J, et al. No change in indices of glucose regulation or insulin resistance after 6 months of daily consumption of sugar sweetened or diet beverages. Endocr Rev. 2016;37(2). doi:10.1210/endo-meetings.2016.DGM.8.SUN-688 | Publication status
5 | Appelhans BM, Baylin A, Huang MH, et al. Beverage Intake and Metabolic Syndrome Risk Over 14 Years: The Study of Women’s Health Across the Nation. J Acad Nutr Diet. 2017;117(4):554-562. doi:10.1016/j.jand.2016.10.011 | Outcome
6 | Araki R, Fujie K, Yuine N, et al. Olive leaf tea is beneficial for lipid metabolism in adults with prediabetes: an exploratory randomized controlled trial. Nutr Res. 2019;67:60-66. doi:10.1016/j.nutres.2019.05.003 | Intervention/exposure
7 | Arnberg K, Mølgaard C, Michaelsen KF, Jensen SM, Trolle E, Larnkjær A. Skim milk, whey, and casein increase body weight and whey and casein increase the plasma Cpeptide concentration in overweight adolescents. J Nutr. 2012;142(12):2083-2090. doi:10.3945/jn.112.161208 | Intervention/exposure
8 | Auerbach BJ, Littman AJ, Tinker L, et al. Associations of 100% fruit juice versus whole fruit with hypertension and diabetes risk in postmenopausal women: Results from the Women’s Health Initiative. Prev Med. 2017;105:212-218. doi:10.1016/j.ypmed.2017.08.031 | Intervention/exposure
9 | Azadbakht L, Nurbakhsh S. Effect of soy drink replacement in a weight reducing diet on anthropometric values and blood pressure among overweight and obese female youths. Asia Pac J Clin Nutr. 2011;20(3):383-389. | Outcome
10 | Azzini E, Venneria E, Ciarapica D, et al. Effect of Red Orange Juice Consumption on Body Composition and Nutritional Status in Overweight/Obese Female: A Pilot Study. Oxid Med Cell Longev. 2017;2017:1672567. doi:10.1155/2017/1672567 | Study design
11 | Babio N, Becerra-Tomás N, Martínez-González MÁ, et al. Consumption of Yogurt, Low-Fat Milk, and Other Low-Fat Dairy Products Is Associated with Lower Risk of Metabolic Syndrome Incidence in an Elderly Mediterranean Population. J Nutr. 2015;145(10):2308-2316. doi:10.3945/jn.115.214593 | Intervention/exposure
12 | Bahorun T, Luximon-Ramma A, Neergheen-Bhujun VS, et al. The effect of black tea on risk factors of cardiovascular disease in a normal population. Prev Med. 2012;54 Suppl:S98-S102. doi:10.1016/j.ypmed.2011.12.009 | Intervention/exposure
13 | Balk L, Hoekstra T, Twisk J. Relationship between long-term coffee consumption and components of the metabolic syndrome: the Amsterdam Growth and Health Longitudinal Study. Eur J Epidemiol. 2009;24(4):203-209. doi:10.1007/s10654-0099323-1 | Intervention/exposure
14 | Banini AE, Boyd LC, Allen JC, Allen HG, Sauls DL. Muscadine grape products intake, diet and blood constituents of non-diabetic and type 2 diabetic subjects. Nutrition. 2006;22(11-12):1137-1145. doi:10.1016/j.nut.2006.08.012 | Outcome
15 | Barr SI, McCarron DA, Heaney RP, et al. Effects of increased consumption of fluid milk on energy and nutrient intake, body weight, and cardiovascular risk factors in healthy older adults. J Am Diet Assoc. 2000;100(7):810-817. doi:10.1016/S00028223(00)00236-4 | Intervention/exposure
16 | Barr SI, McCarron DA, Heaney RP, et al. Effects of increased consumption of fluid milk on energy and nutrient intake, body weight, and cardiovascular risk factors in healthy older adults. J Am Diet Assoc. 2000;100(7):810-817. doi:10.1016/S00028223(00)00236-4 | Duplicate
17 | Barrio-Lopez MT, Martinez-Gonzalez MA, Fernandez-Montero A, Beunza JJ, Zazpe I, Bes-Rastrollo M. Prospective study of changes in sugar-sweetened beverage consumption and the incidence of the metabolic syndrome and its components: the SUN cohort. Br J Nutr. 2013;110(9):1722-1731. doi:10.1017/S0007114513000822 | Outcome
18 | Basu A, Betts NM, Mulugeta A, Tong C, Newman E, Lyons TJ. Green tea supplementation increases glutathione and plasma antioxidant capacity in adults with the metabolic syndrome. Nutr Res. 2013;33(3):180-187. doi:10.1016/j.nutres.2012.12.010 | Intervention/exposure
19 | Basu A, Du M, Sanchez K, et al. Green tea minimally affects biomarkers of inflammation in obese subjects with metabolic syndrome. Nutrition. 2011;27(2):206-213. doi:10.1016/j.nut.2010.01.015 | Intervention/exposure
20 | Basu A, Sanchez K, Leyva MJ, et al. Green tea supplementation affects body weight, lipids, and lipid peroxidation in obese subjects with metabolic syndrome. J Am Coll Nutr. 2010;29(1):31-40. doi:10.1080/07315724.2010.10719814 | Intervention/exposure
21 | Bellikci-Koyu E, Sarer-Yurekli BP, Akyon Y, et al. Effects of Regular Kefir Consumption on Gut Microbiota in Patients with Metabolic Syndrome: A Parallel-Group, Randomized, Controlled Study. Nutrients. 2019;11(9):2089. doi:10.3390/nu11092089 | Intervention/exposure
22 | Bergholdt HK, Nordestgaard BG, Ellervik C. Milk intake is not associated with low risk of diabetes or overweight-obesity: a Mendelian randomization study in 97,811 Danish individuals. Am J Clin Nutr. 2015;102(2):487-496. doi:10.3945/ajcn.114.105049 | Intervention/exposure
23 | Beydoun MA, Fanelli-Kuczmarski MT, Beydoun HA, et al. Dairy product consumption and its association with metabolic disturbance in a prospective study of urban adults. Br J Nutr. 2018;119(6):706-719. doi:10.1017/S0007114518000028 | Intervention/exposure
24 | Bhupathiraju SN, Pan A, Manson JE, Willett WC, van Dam RM, Hu FB. Changes in coffee intake and subsequent risk of type 2 diabetes: three large cohorts of US men and women. Diabetologia. 2014;57(7):1346-1354. doi:10.1007/s00125-014-3235-7 | Intervention/exposure
25 | Bidel S, Silventoinen K, Hu G, Lee DH, Kaprio J, Tuomilehto J. Coffee consumption, serum gamma-glutamyltransferase and risk of type II diabetes. Eur J Clin Nutr. 2008;62(2):178-185. doi:10.1038/sj.ejcn.1602712 | Intervention/exposure
26 | Boggs DA, Rosenberg L, Ruiz-Narvaez EA, Palmer JR. Coffee, tea, and alcohol intake in relation to risk of type 2 diabetes in African American women. Am J Clin Nutr. 2010;92(4):960-966. doi:10.3945/ajcn.2010.29598 | Intervention/exposure
27 | Bondonno NP, Davey RJ, Murray K, et al. Associations Between Fruit Intake and Risk of Diabetes in the AusDiab Cohort. J Clin Endocrinol Metab. 2021;106(10):e4097e4108. doi:10.1210/clinem/dgab335 | Intervention/exposure
28 | Bonnet F, Tavenard A, Esvan M, et al. Consumption of a Carbonated Beverage with High-Intensity Sweeteners Has No Effect on Insulin Sensitivity and Secretion in Nondiabetic Adults. J Nutr. 2018;148(8):1293-1299. doi:10.1093/jn/nxy100 | Intervention/exposure
29 | Brouwer-Brolsma EM, van Woudenbergh GJ, Oude Elferink SJ, et al. Intake of different types of dairy and its prospective association with risk of type 2 diabetes: The Rotterdam Study. Nutr Metab Cardiovasc Dis. 2016;26(11):987-995. doi:10.1016/j.numecd.2016.08.003 | Intervention/exposure
30 | Bruun JM, Maersk M, Belza A, Astrup A, Richelsen B. Consumption of sucrosesweetened soft drinks increases plasma levels of uric acid in overweight and obese subjects: a 6-month randomised controlled trial. Eur J Clin Nutr. 2015;69(8):949-953. doi:10.1038/ejcn.2015.95 | Other (e.g., duplicative data)
31 | Bundrick SC, Thearle MS, Venti CA, Krakoff J, Votruba SB. Soda consumption during ad libitum food intake predicts weight change. J Acad Nutr Diet. 2014;114(3):444-449. doi:10.1016/j.jand.2013.09.016 | Outcome
32 | Buziau AM, Soedamah-Muthu SS, Geleijnse JM, Mishra GD. Total Fermented Dairy Food Intake Is Inversely Associated with Cardiovascular Disease Risk in Women. J Nutr. 2019;149(10):1797-1804. doi:10.1093/jn/nxz128 | Intervention/exposure
33 | Campos V, Despland C, Brandejsky V, et al. Metabolic Effects of Replacing Sugar-Sweetened Beverages with Artificially-Sweetened Beverages in Overweight Subjects with or without Hepatic Steatosis: A Randomized Control Clinical Trial. Nutrients. 2017;9(3):202. doi:10.3390/nu9030202 | Other (e.g., duplicative data)
34 | Campos V, Despland C, Kreis R, et al. Metabolic effects of replacing sugar-sweetened by artificially sweetened beverages in overweight subjects with or without hepatic steatosis: a randomized control clinical trial. Obes Facts. 2017;10:190-191. | Publication status
35 | Carroll SJ, Niyonsenga T, Coffee NT, Taylor AW, Daniel M. Associations between local descriptive norms for overweight/obesity and insufficient fruit intake, individual-level diet, and 10-year change in body mass index and glycosylated haemoglobin in an Australian cohort. Int J Behav Nutr Phys Act. 2018;15(1):44. doi:10.1186/s12966-018-0675-3 | Outcome
36 | Cesar T, Fidelix M, Sivieri K, Millenkovic D. Daily consumption of orange juice modulated intestinal microbiota and improved glucose and lipids metabolism in women. Proc Nutr Soc. 2020;79:(OCE2):E634. doi:10.1017/S0029665120005832 | Study design
37 | Chatterjee S, Roy N, Saha A, et al. Black tea consumption enhance antioxidant status, reduce inflammatory stress vis-a-vis insulin resistance: Hint from a small clinical cohort study on pre-diabetic subjects. Int J Pharm Sci Rev Res. 2014;28:278-283. | Country
38 | Chen Y, Feng R, Yang X, et al. Yogurt improves insulin resistance and liver fat in obese women with nonalcoholic fatty liver disease and metabolic syndrome: a randomized controlled trial. Am J Clin Nutr. 2019;109(6):1611-1619. doi:10.1093/ajcn/nqy358 | Comparator
39 | Cho HJ, Okekunle AP, Yie GE, et al. Association of coffee consumption with type 2 diabetes and glycemic traits: a Mendelian randomization study. Nutr Res Pract. 2023;17(4):789-802. doi:10.4162/nrp.2023.17.4.789 | Intervention/exposure
40 | Cho Y, Ryu S, Kim R, Shin MJ, Oh H. Ultra-processed Food Intake and Risk of Type 2 Diabetes in Korean Adults. J Nutr. 2024;154(1):243-251. doi:10.1016/j.tjnut.2023.11.021 | Duplicate
41 | Cordova R, Viallon V, Fontvieille E, et al. Consumption of ultra-processed foods and risk of multimorbidity of cancer and cardiometabolic diseases: a multinational cohort study. Lancet Reg Health Eur. 2023;35:100771. doi:10.1016/j.lanepe.2023.100771 | Intervention/exposure
42 | Corrêa TAF, Tobaruela EC, Capetini VC, et al. Blood orange juice intake changes specific bacteria of gut microbiota associated with cardiometabolic biomarkers. Front Microbiol. 2023;14:1199383. doi:10.3389/fmicb.2023.1199383 | Study design
43 | Corrêa TAF, Rogero MM, Mioto BM, et al. Paper-filtered coffee increases cholesterol and inflammation biomarkers independent of roasting degree: a clinical trial. Nutrition. 2013;29:977-81. doi:10.1016/j.nut.2013.01.003 | Comparator
44 | Creighton S, Jay M. Are non-nutritive sweetened beverages comparable to water in weight loss trials?. J Clin Outcomes Manag. 2014;21:490-492. | Study design
45 | Daily JW, Liu M, Park S. High genetic risk scores of SLIT3, PLEKHA5 and PPP2R2C variants increased insulin resistance and interacted with coffee and caffeine consumption in middle-aged adults. Nutr Metab Cardiovasc Dis. 2019;29(1):79-89. doi:10.1016/j.numecd.2018.09.009 | Study design
46 | de Moraes MM, Mediano MFF, de Souza RAG, Moura AS, da Veiga GV, Sichieri R. Discouraging soft drink consumption reduces blood glucose and cholesterol of Brazilian elementary students: Secondary analysis of a randomized controlled trial. Prev Med. 2017;100:223-228. doi:10.1016/j.ypmed.2017.04.035 | Intervention/exposure
47 | De B, Shrivastav A, Das T, Goswami TK. Physicochemical and nutritional assessment of soy milk and soymilk products and comparative evaluation of their effects on blood gluco-lipid profile. Applied Food Research. 2022;2(2):100146. doi:https://doi.org/10.1016/j.afres.2022.100146 | Study design
48 | Dhingra R, Sullivan L, Jacques PF, et al. Soft drink consumption and risk of developing cardiometabolic risk factors and the metabolic syndrome in middle-aged adults in the community [published correction appears in Circulation. 2007 Dec 4;116(23):e557]. Circulation. 2007;116(5):480-488. doi:10.1161/CIRCULATIONAHA.107.689935 | Outcome
49 | Díaz-López A, Bulló M, Martínez-González MA, et al. Dairy product consumption and risk of type 2 diabetes in an elderly Spanish Mediterranean population at high cardiovascular risk. Eur J Nutr. 2016;55(1):349-360. doi:10.1007/s00394-015-0855-8 | Intervention/exposure
50 | Ding M, Pan A, Manson JE, et al. Consumption of soy foods and isoflavones and risk of type 2 diabetes: a pooled analysis of three US cohorts. Eur J Clin Nutr. 2016;70(12):1381-1387. doi:10.1038/ejcn.2016.117 | Intervention/exposure
51 | Dong XX, Wang RR, Liu JY, Ma QH, Pan CW. Habitual tea consumption and 5-year incident metabolic syndrome among older adults: a community-based cohort study. BMC Geriatr. 2021;21(1):728. doi:10.1186/s12877-021-02707-8 | Intervention/exposure
52 | Doo T, Morimoto Y, Steinbrecher A, Kolonel LN, Maskarinec G. Coffee intake and risk of type 2 diabetes: the Multiethnic Cohort. Public Health Nutr. 2014;17(6):1328-1336. doi:10.1017/S1368980013000487 | Intervention/exposure
53 | Dourado GK, Cesar TB. Investigation of cytokines, oxidative stress, metabolic, and inflammatory biomarkers after orange juice consumption by normal and overweight subjects. Food Nutr Res. 2015;59:28147. doi:10.3402/fnr.v59.28147 | Study design
54 | Driessen MT, Koppes LL, Veldhuis L, Samoocha D, Twisk JW. Coffee consumption is not related to the metabolic syndrome at the age of 36 years: the Amsterdam Growth and Health Longitudinal Study. Eur J Clin Nutr. 2009;63(4):536-542. doi:10.1038/ejcn.2008.6 | Intervention/exposure
55 | Drouin-Chartier JP, Hernández-Alonso P, Guasch-Ferré M, et al. Dairy consumption, plasma metabolites, and risk of type 2 diabetes. Am J Clin Nutr. 2021;114(1):163-174. doi:10.1093/ajcn/nqab047 | Intervention/exposure
56 | Drouin-Chartier JP, Li Y, Ardisson Korat AV, et al. Changes in dairy product consumption and risk of type 2 diabetes: results from 3 large prospective cohorts of US men and women. Am J Clin Nutr. 2019;110(5):1201-1212. doi:10.1093/ajcn/nqz180 | Intervention/exposure
57 | Drouin-Chartier JP, Gagnon J, Labonté MÈ, et al. Impact of milk consumption on cardiometabolic risk in postmenopausal women with abdominal obesity. Nutr J. 2015;14:12. doi:10.1186/1475-2891-14-12 | Intervention/exposure
58 | Duffey KJ, Gordon-Larsen P, Steffen LM, Jacobs DR Jr, Popkin BM. Drinking caloric beverages increases the risk of adverse cardiometabolic outcomes in the Coronary Artery Risk Development in Young Adults (CARDIA) Study. Am J Clin Nutr. 2010;92(4):954-959. doi:10.3945/ajcn.2010.29478 | Outcome
59 | El-Elimat T, Qasem WM, Al-Sawalha NA, et al. A Prospective Non-Randomized Open-Label Comparative Study of The Effects of Matcha Tea on Overweight and Obese Individuals: A Pilot Observational Study. Plant Foods Hum Nutr. 2022;77(3):447-454. doi:10.1007/s11130-022-00998-9 | Intervention/exposure
60 | Ellis AC, Mehta T, Nagabooshanam VA, Dudenbostel T, Locher JL, Crowe-White KM. Daily 100% watermelon juice consumption and vascular function among postmenopausal women: A randomized controlled trial. Nutr Metab Cardiovasc Dis. 2021;31(10):2959-2968. doi:10.1016/j.numecd.2021.06.022 | Comparator
61 | Elwood PC, Pickering JE, Fehily AM. Milk and dairy consumption, diabetes and the metabolic syndrome: the Caerphilly prospective study. J Epidemiol Community Health. 2007;61(8):695-698. doi:10.1136/jech.2006.053157 | Intervention/exposure
62 | Esfandiar Z, Hosseini-Esfahani F, Mirmiran P, Azizi F. Higher dietary flavonol and isoflavonoid intakes are associated with lower incidence of type 2 diabetes. Int J Vitam Nutr Res. doi:10.1024/0300-9831/a000782 | Intervention/exposure
63 | Fagherazzi G, Gusto G, Mancini FR, et al. Determinants of 20-year non-progression to Type 2 diabetes in women at very high risk: the E3N cohort study. Diabet Med. 2018;35(12):1716-1721. doi:10.1111/dme.13774 | Intervention/exposure
64 | Fagherazzi G, Vilier A, Saes Sartorelli D, Lajous M, Balkau B, Clavel-Chapelon F. Consumption of artificially and sugar-sweetened beverages and incident type 2 diabetes in the Etude Epidemiologique aupres des femmes de la Mutuelle Generale de l’Education Nationale-European Prospective Investigation into Cancer and Nutrition cohort. Am J Clin Nutr. 2013;97(3):517-523. doi:10.3945/ajcn.112.050997 | Duplicate
65 | Faghih S, Hedayati M, Abadi A, Kimiagar M. Comparing the effects of cow’s milk, and calcium supplementation on components of the metabolic syndrome in overweight or obese women. Iranian J Endocrinology and Metabolism. 2013;14(5):430-436. | Intervention/exposure
66 | Fernandez-Cao JC, Arija V, Aranda N, et al. Heme iron intake and risk of new-onset diabetes in a Mediterranean population at high risk of cardiovascular disease: an observational cohort analysis. BMC Public Health. 2013;13:1042. doi:10.1186/14712458-13-1042 | Intervention/exposure
67 | Ferreira I, Twisk JW, van Mechelen W, Kemper HC, Stehouwer CD. Development of fatness, fitness, and lifestyle from adolescence to the age of 36 years: determinants of the metabolic syndrome in young adults: the amsterdam growth and health longitudinal study. Arch Intern Med. 2005;165(1):42-48. doi:10.1001/archinte.165.1.42 | Intervention/exposure
68 | Ferreira-Pêgo C, Babio N, Bes-Rastrollo M, et al. Frequent Consumption of Sugar- and Artificially Sweetened Beverages and Natural and Bottled Fruit Juices Is Associated with an Increased Risk of Metabolic Syndrome in a Mediterranean Population at High Cardiovascular Disease Risk. J Nutr. 2016;146(8):1528-1536. doi:10.3945/jn.116.230367 | Outcome
69 | Fidélix M, Milenkovic D, Sivieri K, Cesar T. Microbiota modulation and effects on metabolic biomarkers by orange juice: a controlled clinical trial. Food Funct. 2020;11(2):1599-1610. doi:10.1039/c9fo02623a | Study design
70 | Flieh SM, Miguel-Berges ML, Huybrechts I, et al. Associations between food portion sizes, insulin resistance, VO2 max and metabolic syndrome in European adolescents: The HELENA study. Nutr Metab Cardiovasc Dis. 2022;32(9):2061-2073. doi:10.1016/j.numecd.2022.05.017 | Study design
71 | Floegel A, Pischon T, Bergmann MM, Teucher B, Kaaks R, Boeing H. Coffee consumption and risk of chronic disease in the European Prospective Investigation into Cancer and Nutrition (EPIC)-Germany study. Am J Clin Nutr. 2012;95(4):901-908. doi:10.3945/ajcn.111.023648 | Intervention/exposure
72 | Fonollá J, López-Huertas E, Machado FJ, et al. Milk enriched with “healthy fatty acids” improves cardiovascular risk markers and nutritional status in human volunteers. Nutrition. 2009;25(4):408-414. doi:10.1016/j.nut.2008.10.008 | Intervention/exposure
73 | Fresan U, Gea A, Bes-Rastrollo M, Basterra-Gortari FJ, Carlos S, Martinez-Gonzalez MA. Substitution of water or fresh juice for bottled juice and type 2 diabetes incidence: The SUN cohort study. Nutr Metab Cardiovasc Dis. 2017;27(10):874-880. doi:10.1016/j.numecd.2017.07.010 | Intervention/exposure
74 | Fuhrman BJ, Smit E, Crespo CJ, Garcia-Palmieri MR. Coffee intake and risk of incident diabetes in Puerto Rican men: results from the Puerto Rico Heart Health Program. Public Health Nutr. 2009;12(6):842-848. doi:10.1017/S1368980008003303 | Intervention/exposure
75 | Fujioka K, Greenway F, Sheard J, Ying Y. The effects of grapefruit on weight and insulin resistance: relationship to the metabolic syndrome. J Med Food. 2006;9(1):49-54. doi:10.1089/jmf.2006.9.49 | Intervention/exposure
76 | Fumeron F, Lamri A, Abi Khalil C, et al. Dairy consumption and the incidence of hyperglycemia and the metabolic syndrome: results from a french prospective study, Data from the Epidemiological Study on the Insulin Resistance Syndrome (DESIR). Diabetes Care. 2011;34(4):813-817. doi:10.2337/dc10-1772 | Intervention/exposure
77 | Garcia DO, Morrill KE, Aceves B, et al. Feasibility and acceptability of a beverage intervention for Hispanic adults: results from a pilot randomized controlled trial. Public Health Nutr. 2019;22(3):542-552. doi:10.1017/S1368980018003051 | Outcome
78 | Gilbert JA, Joanisse DR, Chaput JP, et al. Milk supplementation facilitates appetite control in obese women during weight loss: a randomised, single-blind, placebocontrolled trial. Br J Nutr. 2011;105(1):133-143. doi:10.1017/S0007114510003119 | Comparator
79 | Gonçalinho GHF, Nascimento JRO, Mioto BM, et al. Effects of Coffee on Sirtuin-1, Homocysteine, and Cholesterol of Healthy Adults: Does the Coffee Powder Matter?. J Clin Med. 2022;11(11):2985. doi:10.3390/jcm11112985 | Comparator
80 | Goto A, Song Y, Chen BH, Manson JE, Buring JE, Liu S. Coffee and caffeine consumption in relation to sex hormone-binding globulin and risk of type 2 diabetes in postmenopausal women. Diabetes. 2011;60(1):269-275. doi:10.2337/db10-1193 | Intervention/exposure
81 | Green BP, Stevenson EJ, Rumbold PLS. Metabolic, endocrine and appetite-related responses to acute and daily milk snack consumption in healthy, adolescent males. Appetite. 2017;108:93-103. doi:10.1016/j.appet.2016.09.029 | Comparator
82 | Guess N, Wijesuriya M, Vasantharajah L, et al. The effect of dietary changes on distinct components of the metabolic syndrome in a young Sri Lankan population at high risk of CVD. Br J Nutr. 2016;116(4):719-727. doi:10.1017/S0007114516002476 | Intervention/exposure
83 | Gul S, Khatoon H, Ahmed N, Rashid H, Mirza AZ. Possible role of grape fruit in controlling hyperglycemia and associated complications: Better glycemic control in healthy subjects through fruits fibers as compared to fruit juices. Bangladesh Journal of Medical Science. 2020;19(3):480-485. doi:10.3329/bjms.v19i3.45866 | Outcome
84 | Guo H, Zhong R, Liu Y, et al. Effects of bayberry juice on inflammatory and apoptotic markers in young adults with features of non-alcoholic fatty liver disease. Nutrition. 2014;30(2):198-203. doi:10.1016/j.nut.2013.07.023 | Comparator
85 | Hägele FA, Büsing F, Nas A, et al. High orange juice consumption with or in-between three meals a day differently affects energy balance in healthy subjects. Nutr Diabetes. 2018;8(1):19. doi:10.1038/s41387-018-0031-3 | Comparator
86 | Ham JY, Shon YH. Natural Magnesium-Enriched Deep-Sea Water Improves Insulin Resistance and the Lipid Profile of Prediabetic Adults: A Randomized, Double-Blinded Crossover Trial. Nutrients. 2020;12(2):515. doi:10.3390/nu12020515 | Comparator
87 | Hamer M, Witte DR, Mosdøl A, Marmot MG, Brunner EJ. Prospective study of coffee and tea consumption in relation to risk of type 2 diabetes mellitus among men and women: the Whitehall II study. Br J Nutr. 2008;100(5):1046-1053. doi:10.1017/S0007114508944135 | Intervention/exposure
88 | Harrold JA, Hill S, Radu C, et al. Non-nutritive sweetened beverages versus water after a 52-week weight management programme: a randomised controlled trial. Int J Obes (Lond). 2024;48(1):83-93. doi:10.1038/s41366-023-01393-3 | Duplicate
89 | Hayashino Y, Fukuhara S, Okamura T, Tanaka T, Ueshima H; HIPOP-OHP Research Group. High oolong tea consumption predicts future risk of diabetes among Japanese male workers: a prospective cohort study. Diabet Med. 2011;28(7):805-810. doi:10.1111/j.1464-5491.2011.03239.x | Intervention/exposure
90 | Hiltunen LA. Are there associations between coffee consumption and glucose tolerance in elderly subjects?. Eur J Clin Nutr. 2006;60(10):1222-1225. doi:10.1038/sj.ejcn.1602441 | Intervention/exposure
91 | Hinkle SN, Rawal S, Bjerregaard AA, et al. A prospective study of artificially sweetened beverage intake and cardiometabolic health among women at high risk. Am J Clin Nutr. 2019;110(1):221-232. doi:10.1093/ajcn/nqz094 | Health status
92 | Hirata A, Ohnaka K, Tashiro N, et al. Effect modification of green tea on the association between rice intake and the risk of diabetes mellitus: a prospective study in Japanese men and women. Asia Pac J Clin Nutr. 2017;26(3):545-555. doi:10.6133/apjcn.042016.04 | Intervention/exposure
93 | Hirota T, Kawasaki I, Hirota K, et al. P267 - Milk intake accompanied with higher intake of vitamin D might efficiently decrease body fat mass and increase lean mass during moderate weight loss in normal weight young Japanese women. Osteoporosis International. 2010;21:S98. doi:10.1007/s00198-010-1247-9 | Publication status
94 | Hjellvik V, Tverdal A, Strøm H. Boiled coffee intake and subsequent risk for type 2 diabetes. Epidemiology. 2011;22(3):418-421. doi:10.1097/EDE.0b013e31821083e3 | Intervention/exposure
95 | Hollands WJ, Armah CN, Doleman JF, Perez-Moral N, Winterbone MS, Kroon PA. 4Week consumption of anthocyanin-rich blood orange juice does not affect LDLcholesterol or other biomarkers of CVD risk and glycaemia compared with standard orange juice: a randomised controlled trial. Br J Nutr. 2018;119(4):415-421. doi:10.1017/S0007114517003865 | Comparator
96 | Hollis JH, Houchins JA, Blumberg JB, Mattes RD. Effects of concord grape juice on appetite, diet, body weight, lipid profile, and antioxidant status of adults. J Am Coll Nutr. 2009;28(5):574-582. doi:10.1080/07315724.2009.10719789 | Intervention/exposure
97 | Hong X, Xu F, Wang Z, Liang Y, Li J. Dietary patterns and the incidence of hyperglyacemia in China. Public Health Nutr. 2016;19(1):131-141. doi:10.1017/S1368980015000774 | Intervention/exposure
98 | Hosseinpour-Niazi S, Aghayan M, Mirmiran P, Azizi F. Does weight change modify the association between the consumption of sugar-sweetened beverages and 100% fruit juice and the risk of metabolic syndrome?. Clin Nutr. 2021;40(10):5261-5268. doi:10.1016/j.clnu.2021.08.017 | Outcome
99 | Hou C, Zeng Y, Chen W, et al. Medical conditions associated with coffee consumption: Disease-trajectory and comorbidity network analyses of a prospective cohort study in UK Biobank. Am J Clin Nutr. 2022;116(3):730-740. doi:10.1093/ajcn/nqac148 | Outcome
100 | Hruby A, Ma J, Rogers G, Meigs JB, Jacques PF. Associations of Dairy Intake with Incident Prediabetes or Diabetes in Middle-Aged Adults Vary by Both Dairy Type and Glycemic Status. J Nutr. 2017;147(9):1764-1775. doi:10.3945/jn.117.253401 | Intervention/exposure
101 | Hsia DS, Zhang DJ, Beyl RS, Greenway FL, Khoo C. Effect of daily consumption of cranberry beverage on insulin sensitivity and modification of cardiovascular risk factors in adults with obesity: a pilot, randomised, placebo-controlled study. Br J Nutr. 2020;124(6):577-585. doi:10.1017/S0007114520001336 | Intervention/exposure
102 | Hu G, Jousilahti P, Peltonen M, Bidel S, Tuomilehto J. Joint association of coffee consumption and other factors to the risk of type 2 diabetes: a prospective study in Finland. Int J Obes (Lond). 2006;30(12):1742-1749. doi:10.1038/sj.ijo.0803341 | Intervention/exposure
103 | Hur YI, Park H, Kang JH, et al. Associations between Sugar Intake from Different Food Sources and Adiposity or Cardio-Metabolic Risk in Childhood and Adolescence: The Korean Child-Adolescent Cohort Study. Nutrients. 2015;8(1):20. doi:10.3390/nu8010020 | Intervention/exposure
104 | Ibsen DB, Laursen ASD, Lauritzen L, Tjønneland A, Overvad K, Jakobsen MU. Substitutions between dairy product subgroups and risk of type 2 diabetes: the Danish Diet, Cancer and Health cohort. Br J Nutr. 2017;118(11):989-997. doi:10.1017/S0007114517002896 | Intervention/exposure
105 | Ibsen DB, Overvad K, Laursen ASD, et al. Changes in intake of dairy product subgroups and risk of type 2 diabetes: modelling specified food substitutions in the Danish Diet, Cancer and Health cohort. Eur J Nutr. 2021;60(6):3449-3459. doi:10.1007/s00394-021-02524-0 | Intervention/exposure
106 | Indrayani, Rahmadi A, Syarifah R, et al. Effect of dates and 7dates on blood glucose levels among adolescent girls: A randomized controlled trial. Pakistan J Medical and Health Sciences. 2021;15:393-398. | Intervention/exposure
107 | Iso H, Date C, Wakai K, Fukui M, Tamakoshi A; JACC Study Group. The relationship between green tea and total caffeine intake and risk for self-reported type 2 diabetes among Japanese adults. Ann Intern Med. 2006;144(8):554-562. doi:10.7326/00034819-144-8-200604180-00005 | Intervention/exposure
108 | Jacobo Cejudo MG, Ochoa-Rosales C, Ahmadizar F, Kavousi M, Geleijnse JM, Voortman T. The healthy beverage index is not associated with insulin resistance, prediabetes and type 2 diabetes risk in the Rotterdam Study. Eur J Nutr. 2023;62(7):3021-3031. doi:10.1007/s00394-023-03209-6 | Intervention/exposure
109 | Jacobs S, Kröger J, Floegel A, et al. Evaluation of various biomarkers as potential mediators of the association between coffee consumption and incident type 2 diabetes in the EPIC-Potsdam Study. Am J Clin Nutr. 2014;100(3):891-900. doi:10.3945/ajcn.113.080317 | Intervention/exposure
110 | Jarman M, Mathe N, Ramazani F, et al. Dietary Patterns Prior to Pregnancy and Associations with Pregnancy Complications. Nutrients. 2018;10(7):914. doi:10.3390/nu10070914 | Intervention/exposure
111 | Jeon J, Jang J, Park K. Effects of Consuming Calcium-Rich Foods on the Incidence of Type 2 Diabetes Mellitus. Nutrients. 2018;11(1):31. doi:10.3390/nu11010031 | Intervention/exposure
112 | Jin R, Collin L, Vos M, Welsh J. Replacement of sugar-sweetened beverages with water and its impact on insulin sensitivity among overweight adolescents and young adults. FASEB J. 2015;29(S1). doi:10.1096/fasebj.29.1_supplement.584.12 | Publication status
113 | Jin T, Youn J, Kim AN, et al. Interactions of Habitual Coffee Consumption by Genetic Polymorphisms with the Risk of Prediabetes and Type 2 Diabetes Combined. Nutrients. 2020;12(8):2228. doi:10.3390/nu12082228 | Intervention/exposure
114 | Johansson I, Esberg A, Nilsson LM, Jansson JH, Wennberg P, Winkvist A. Dairy Product Intake and Cardiometabolic Diseases in Northern Sweden: A 33-Year Prospective Cohort Study. Nutrients. 2019;11(2):284. doi:10.3390/nu11020284 | Intervention/exposure
115 | Johansson I, Nilsson LM, Esberg A, Jansson JH, Winkvist A. Dairy intake revisited - associations between dairy intake and lifestyle related cardio-metabolic risk factors in a high milk consuming population. Nutr J. 2018;17(1):110. doi:10.1186/s12937-018-0418y | Intervention/exposure
116 | Jung HJ, Han SN, Song S, Paik HY, Baik HW, Joung H. Association between adherence to the Korean Food Guidance System and the risk of metabolic abnormalities in Koreans. Nutr Res Pract. 2011;5(6):560-568. doi:10.4162/nrp.2011.5.6.560 | Study design
117 | Juturu V, Wilson D, Evans M, Kasper K. Effect of a cranberry beverage on insulinotropic response in moderately hypercholesterolemic overweight/obese adults: a randomized, Double-blind, Placebo-controlled clinical trial. Endocrine Practice. 2011;17:19A. | Publication status
118 | Kang Y, Kim J. Soft drink consumption is associated with increased incidence of the metabolic syndrome only in women. Br J Nutr. 2017;117(2):315-324. doi:10.1017/S0007114517000046 | Outcome
119 | Karimnezhad N, Mahdavi Roshan M, Izaddoust, et al. The simultaneous effects of green coffee and combine exercise training on body composition and glucose homeostasis in obese and overweight women. J Med Plants. 2019;18 (72):215-227. doi:10.29252/JMP.4.72.215 | Intervention/exposure
120 | Kato M, Noda M, Inoue M, Kadowaki T, Tsugane S; JPHC Study Group. Psychological factors, coffee and risk of diabetes mellitus among middle-aged Japanese: a populationbased prospective study in the JPHC study cohort [published correction appears in Endocr J.2011;58(5):421]. Endocr J. 2009;56(3):459-468. doi:10.1507/endocrj.k09e-003 | Intervention/exposure
121 | Keshavarz SA, Nourieh Z, Attar MJ, Azadbakht L. Effect of Soymilk Consumption on Waist Circumference and Cardiovascular Risks among Overweight and Obese Female Adults. Int J Prev Med. 2012;3(11):798-805. | Intervention/exposure
122 | Khorraminezhad L, Bilodeau JF, Greffard K, Larose J, Rudkowska I. Impact of Dairy Intake on Plasma F_2_-IsoProstane Profiles in Overweight Subjects with Hyperinsulinemia: A Randomized Crossover Trial. Nutrients. 2021;13(6):2088. doi:10.3390/nu13062088 | Intervention/exposure
123 | Kim AN, Cho HJ, Youn J, et al. Coffee Consumption, Genetic Polymorphisms, and the Risk of Type 2 Diabetes Mellitus: A Pooled Analysis of Four Prospective Cohort Studies. Int J Environ Res Public Health. 2020;17(15):5379. doi:10.3390/ijerph17155379 | Intervention/exposure
124 | Kim D, Kim J. Dairy consumption is associated with a lower incidence of the metabolic syndrome in middle-aged and older Korean adults: the Korean Genome and Epidemiology Study (KoGES). Br J Nutr. 2017;117(1):148-160. doi:10.1017/S000711451600444X | Intervention/exposure
125 | Kim J. Dairy food consumption is inversely associated with the risk of the metabolic syndrome in Korean adults. J Hum Nutr Diet. 2013;26 Suppl 1:171-179. doi:10.1111/jhn.12098 | Study design
126 | Kim MJ, Kim JI, Ryu CH, Kang MJ. Effects of Fermented Beverage in Subjects with Metabolic Syndrome. Prev Nutr Food Sci. 2021;26(1):12-20. doi:10.3746/pnf.2021.26.1.12 | Intervention/exposure
127 | Koloverou E, Panagiotakos DB, Pitsavos C, et al. The evaluation of inflammatory and oxidative stress biomarkers on coffee-diabetes association: results from the 10-year follow-up of the ATTICA Study (2002-2012). Eur J Clin Nutr. 2015;69(11):1220-1225. doi:10.1038/ejcn.2015.98 | Intervention/exposure
128 | Koloverou E, Panagiotakos DB, Pitsavos C, et al. The long term effect of dietary habits and physical activity on type 2 diabetes incidence: 10-year follow up of the ATTICA study (2002-2012): Diet, physical activity and diabetes. Hell J Atheroscler. 2018;9:5-16. | Intervention/exposure
129 | Kummer K, Jensen PN, Kratz M, et al. Full-Fat Dairy Food Intake is Associated with a Lower Risk of Incident Diabetes Among American Indians with Low Total Dairy Food Intake. J Nutr. 2019;149(7):1238-1244. doi:10.1093/jn/nxz058 | Intervention/exposure
130 | Kwok MK, Leung GM, Schooling CM. Habitual coffee consumption and risk of type 2 diabetes, ischemic heart disease, depression and Alzheimer’s disease: a Mendelian randomization study. Sci Rep. 2016;6:36500. doi:10.1038/srep36500 | Intervention/exposure
131 | Lee HA, Son N, Lee WK, Park H. A Diabetes-Related Dietary Pattern Is Associated with Incident Diabetes in Obese Men in the Korean Genome Epidemiology Study. J Nutr. 2019;149(2):323-329. doi:10.1093/jn/nxy274 | Intervention/exposure
132 | Lee JH, Oh MK, Lim JT, Kim HG, Lee WJ. Effect of Coffee Consumption on the Progression of Type 2 Diabetes Mellitus among Prediabetic Individuals. Korean J Fam Med. 2016;37(1):7-13. doi:10.4082/kjfm.2016.37.1.7 | Intervention/exposure
133 | Lee JK, Kim K, Ahn Y, Yang M, Lee JE. Habitual coffee intake, genetic polymorphisms, and type 2 diabetes. Eur J Endocrinol. 2015;172(5):595-601. doi:10.1530/EJE-14-0805 | Intervention/exposure
134 | Lee KW, Shin D. A Healthy Beverage Consumption Pattern Is Inversely Associated with the Risk of Obesity and Metabolic Abnormalities in Korean Adults. J Med Food. 2018;21(9):935-945. doi:10.1089/jmf.2017.0119 | Study design
135 | Leermakers ET, Felix JF, Jaddoe VW, Raat H, Franco OH, Kiefte-de Jong JC. Sugarcontaining beverage intake at the age of 1 year and cardiometabolic health at the age of 6 years: the Generation R Study. Int J Behav Nutr Phys Act. 2015;12:114. doi:10.1186/s12966-015-0278-1 | Outcome
136 | Li M, Yang L, Ma M, Liu Y. Improving the metabolism of glucose and lipids in patients with prediabetes by affecting the gut microbiota. Diabetes Metab Res Rev. 2017;33:S1. doi:10.1002/dmrr.2948 | Publication status
137 | Li X, Zeng J, Chen B, et al. Daily higher tea consumption is associated with a reduced risk of type 2 diabetes: A cohort study and updated systematic review and meta-analysis. Nutr Res. 2023;118:116-127. doi:10.1016/j.nutres.2023.08.002 | Intervention/exposure
138 | Li X, Yin J, Zhu Y, et al. Effects of whole milk supplementation on gut microbiota and cardiometabolic biomarkers in subjects with and without lactose malabsorption. Nutrients. 2018;10(10):1403. doi:10.3390/nu10101403 | Study design
139 | Li Y, Wang DD, Ley SH, et al. Time Trends of Dietary and Lifestyle Factors and Their Potential Impact on Diabetes Burden in China [published correction appears in Diabetes Care. 2018 May;41(5):1116. doi: 10.2337/dc18-er05]. Diabetes Care. 2017;40(12):1685-1694. doi:10.2337/dc17-0571 | Study design
140 | Lima ACD, Cecatti C, Fidélix MP, et al. Effect of Daily Consumption of Orange Juice on the Levels of Blood Glucose, Lipids, and Gut Microbiota Metabolites: Controlled Clinical Trials. J Med Food. 2019;22(2):202-210. doi:10.1089/jmf.2018.0080 | Study design
141 | Liu M, Chen QT, Li ZC, Zhang J, Wang PG, He QQ. Association Between Diet Quality and Cardiometabolic Risk Factor Clustering Stratified by Socioeconomic Status Among Chinese Children. J Acad Nutr Diet. 2021;121(10):1975-1983.e2. doi:10.1016/j.jand.2021.03.009 | Intervention/exposure
142 | Liu S, van der Schouw YT, Soedamah-Muthu SS, Spijkerman AMW, Sluijs I. Intake of dietary saturated fatty acids and risk of type 2 diabetes in the European Prospective Investigation into Cancer and Nutrition-Netherlands cohort: associations by types, sources of fatty acids and substitution by macronutrients. Eur J Nutr. 2019;58(3):11251136. doi:10.1007/s00394-018-1630-4 | Intervention/exposure
143 | Liu X, Xu W, Cai H, et al. Green tea consumption and risk of type 2 diabetes in Chinese adults: the Shanghai Women’s Health Study and the Shanghai Men’s Health Study. Int J Epidemiol. 2018;47(6):1887-1896. doi:10.1093/ije/dyy173 | Country
144 | Löfvenborg JE, Andersson T, Carlsson PO, et al. Sweetened beverage intake and risk of latent autoimmune diabetes in adults (LADA) and type 2 diabetes. Eur J Endocrinol. 2016;175(6):605-614. doi:10.1530/EJE-16-0376 | Study design
145 | Louie JC, Flood VM, Rangan AM, et al. Higher regular fat dairy consumption is associated with lower incidence of metabolic syndrome but not type 2 diabetes. Nutr Metab Cardiovasc Dis. 2013;23(9):816-821. doi:10.1016/j.numecd.2012.08.004 | Intervention/exposure
146 | Lu J, Wang Z. C-reactive protein partially mediates the inverse effect of coffee consumption on risk of type 2 diabetes: Evidence from two-stage Mendelian randomization analysis. Clin Nutr. 2023;42(9):1747-1748. doi:10.1016/j.clnu.2023.07.024 | Intervention/exposure
147 | Luo Y, He L, Ma T, et al. Associations between consumption of three types of beverages and risk of cardiometabolic multimorbidity in UK Biobank participants: a prospective cohort study. BMC Med. 2022;20(1):273. doi:10.1186/s12916-022-02456-4 | Outcome
148 | Ma J, Jacques PF, Meigs JB, et al. Sugar-Sweetened Beverage but Not Diet Soda Consumption Is Positively Associated with Progression of Insulin Resistance and Prediabetes. J Nutr. 2016;146(12):2544-2550. doi:10.3945/jn.116.234047 | Outcome
149 | Ma Z, Hao M. Longitudinal study of the relationship between coffee consumption and type 2 diabetes in Chinese adult residents: Data from China Health and Nutrition Survey. PLoS One. 2021;16(5):e0251377. doi:10.1371/journal.pone.0251377 | Country
150 | Malik VS, Sun Q, van Dam RM, et al. Adolescent dairy product consumption and risk of type 2 diabetes in middle-aged women. Am J Clin Nutr. 2011;94(3):854-861. doi:10.3945/ajcn.110.009621 | Intervention/exposure
151 | Martin KR, Coles KM. Consumption of 100% Tart Cherry Juice Reduces Serum Urate in Overweight and Obese Adults. Curr Dev Nutr. 2019;3(5):nzz011. doi:10.1093/cdn/nzz011 | Intervention/exposure
152 | Martini D, Rosi A, Tassotti M, et al. Effect of coffee and cocoa-based confectionery containing coffee on markers of cardiometabolic health: results from the pocket-4-life project. Eur J Nutr. 2021;60(3):1453-1463. doi:10.1007/s00394-020-02347-5 | Intervention/exposure
153 | Maskarinec G, Kristal BS, Wilkens LR, et al. Risk Factors for Type 2 Diabetes in the Multiethnic Cohort. Can J Diabetes. 2023;47(8):627-635.e2. doi:10.1016/j.jcjd.2023.06.004 | Intervention/exposure
154 | Maskarinec G, Kristal BS, Wilkens LR, et al. Risk Factors for Type 2 Diabetes in the Multiethnic Cohort. Can J Diabetes. 2023;47(8):627-635.e2. doi:10.1016/j.jcjd.2023.06.004 | Duplicate
155 | Mena P, Tassotti M, Rosi A, et al. A comprehensive approach to the bioavailability and cardiometabolic effects of the bioactive compounds present in espresso coffee and confectionery-derived coffee. Proc Nutr Soc. 2020;79(OCE2):E123. doi:10.1017/S0029665120000713 | Publication status
156 | Miranda AM, Steluti J, Fisberg RM, Marchioni DM. Association between Coffee Consumption and Its Polyphenols with Cardiovascular Risk Factors: A Population-Based Study. Nutrients. 2017;9(3):276. doi:10.3390/nu9030276 | Study design
157 | Mirmiran P, Carlström M, Bahadoran Z, Azizi F. Long-term effects of coffee and caffeine intake on the risk of pre-diabetes and type 2 diabetes: Findings from a population with low coffee consumption. Nutr Metab Cardiovasc Dis. 2018;28(12):1261-1266. doi:10.1016/j.numecd.2018.09.001 | Intervention/exposure
158 | Moreira TKB, Santos HCD, Mendes FD, Molina MDCB, Mill JG, Faria CP. Examining the Usage Patterns of Non-Nutritive Sweeteners among Non-Diabetic Individuals: Insights from the Longitudinal Study of Adult Health (ELSA-Brasil). Nutrients. 2023;15(22):4785. doi:10.3390/nu15224785 | Study design
159 | Moreno LA, Bel-Serrat S, Santaliestra-Pasías A, Bueno G. Dairy products, yogurt consumption, and cardiometabolic risk in children and adolescents. Nutr Rev. 2015;73 Suppl 1:8-14. doi:10.1093/nutrit/nuv014 | Study design
160 | Moslehi N, Shab-Bidar S, Mirmiran P, Sadeghi M, Azizi F. Associations between dairy products consumption and risk of type 2 diabetes: Tehran lipid and glucose study. Int J Food Sci Nutr. 2015;66(6):692-699. doi:10.3109/09637486.2015.1034249 | Intervention/exposure
161 | Mueller NT, Odegaard AO, Gross MD, et al. Soy intake and risk of type 2 diabetes in Chinese Singaporeans [corrected] [published correction appears in Eur J Nutr. Eur J Nutr. 2012 Dec;51(8):1041]. Eur J Nutr. 2012;51(8):1033-1040. doi:10.1007/s00394011-0276-2 | Intervention/exposure
162 | Mukamal KJ, MacDermott K, Vinson JA, Oyama N, Manning WJ, Mittleman MA. A 6month randomized pilot study of black tea and cardiovascular risk factors. Am Heart J. 2007;154(4):724.e1-724.e7246. doi:10.1016/j.ahj.2007.07.008 | Intervention/exposure
163 | Muraki I, Imamura F, Manson JE, et al. Fruit consumption and risk of type 2 diabetes: results from three prospective longitudinal cohort studies [published correction appears in BMJ. 2013;347:f6935]. BMJ. 2013;347:f5001. doi:10.1136/bmj.f5001 | Intervention/exposure
164 | Mursu J, Virtanen JK, Tuomainen TP, Nurmi T, Voutilainen S. Intake of fruit, berries, and vegetables and risk of type 2 diabetes in Finnish men: the Kuopio Ischaemic Heart Disease Risk Factor Study. Am J Clin Nutr. 2014;99(2):328-333. doi:10.3945/ajcn.113.069641 | Intervention/exposure
165 | Nakamura Y, Watanabe H, Tanaka A, Yasui M, Nishihira J, Murayama N. Effect of increased daily water intake and hydration on health in Japanese adults. Nutrients. 2020;12(4):1191. doi:10.3390/nu12041191 | Intervention/exposure
166 | Nettleton JA, Harnack LJ, Scrafford CG, Mink PJ, Barraj LM, Jacobs DR Jr. Dietary flavonoids and flavonoid-rich foods are not associated with risk of type 2 diabetes in postmenopausal women. J Nutr. 2006;136(12):3039-3045. doi:10.1093/jn/136.12.3039 | Intervention/exposure
167 | Nettleton JA, Steffen LM, Ni H, Liu K, Jacobs DR Jr. Dietary patterns and risk of incident type 2 diabetes in the Multi-Ethnic Study of Atherosclerosis (MESA). Diabetes Care. 2008;31(9):1777-1782. doi:10.2337/dc08-0760 | Other (e.g., duplicative data)
168 | Ng R, Sutradhar R, Yao Z, Wodchis WP, Rosella LC. Smoking, drinking, diet and physical activity-modifiable lifestyle risk factors and their associations with age to first chronic disease. Int J Epidemiol. 2020;49(1):113-130. doi:10.1093/ije/dyz078 | Intervention/exposure
169 | Nie J, Yu C, Guo Y, et al. Tea consumption and long-term risk of type 2 diabetes and diabetic complications: a cohort study of 0.5 million Chinese adults. Am J Clin Nutr. 2021;114(1):194-202. doi:10.1093/ajcn/nqab006 | Country
170 | Nordestgaard AT, Thomsen M, Nordestgaard BG. Coffee intake and risk of obesity, metabolic syndrome and type 2 diabetes: a Mendelian randomization study. Int J Epidemiol. 2015;44(2):551-565. doi:10.1093/ije/dyv083 | Intervention/exposure
171 | Oba S, Nagata C, Nakamura K, et al. Consumption of coffee, green tea, oolong tea, black tea, chocolate snacks and the caffeine content in relation to risk of diabetes in Japanese men and women. Br J Nutr. 2010;103(3):453-459. doi:10.1017/S0007114509991966 | Intervention/exposure
172 | Ochoa-Rosales C, van der Schaft N, Braun KVE, et al. C-reactive protein partially mediates the inverse association between coffee consumption and risk of type 2 diabetes: The UK Biobank and the Rotterdam study cohorts. Clin Nutr. 2023;42(5):661-669. doi:10.1016/j.clnu.2023.02.024 | Intervention/exposure
173 | O’Connor LM, Lentjes MA, Luben RN, Khaw KT, Wareham NJ, Forouhi NG. Dietary dairy product intake and incident type 2 diabetes: a prospective study using dietary data from a 7-day food diary. Diabetologia. 2014;57(5):909-917. doi:10.1007/s00125-0143176-1 | Intervention/exposure
174 | O’Connor S, Julien P, Weisnagel SJ, Gagnon C, Rudkowska I. Impact of a High Intake of Dairy Product on Insulin Sensitivity in Hyperinsulinemic Adults: A Crossover Randomized Controlled Trial. Curr Dev Nutr. 2019;3(8):nzz083. doi:10.1093/cdn/nzz083 | Intervention/exposure
175 | Odegaard AO, Pereira MA, Koh WP, Arakawa K, Lee HP, Yu MC. Coffee, tea, and incident type 2 diabetes: the Singapore Chinese Health Study. Am J Clin Nutr. 2008;88(4):979-985. doi:10.1093/ajcn/88.4.979 | Intervention/exposure
176 | Ohnaka K, Ikeda M, Maki T, et al. Effects of 16-week consumption of caffeinated and decaffeinated instant coffee on glucose metabolism in a randomized controlled trial. J Nutr Metab. 2012;2012:207426. doi:10.1155/2012/207426 | Intervention/exposure
177 | Ohnaka K, Ikeda M, Maki T, et al. Effects of 16-week consumption of caffeinated and decaffeinated instant coffee on glucose metabolism in a randomized controlled trial. J Nutr Metab. 2012;2012:207426. doi:10.1155/2012/207426 | Duplicate
178 | Olofsson C, Discacciati A, Åkesson A, Orsini N, Brismar K, Wolk A. Changes in fruit, vegetable and juice consumption after the diagnosis of type 2 diabetes: a prospective study in men. Br J Nutr. 2017;117(5):712-719. doi:10.1017/S0007114516002257 | Intervention/exposure
179 | Olsen NJ, Andersen LB, Wedderkopp N, Kristensen PL, Heitmann BL. Intake of liquid and solid sucrose in relation to changes in body fatness over 6 years among 8- to 10year-old children: the European Youth Heart Study. Obes Facts. 2012;5(4):506-512. doi:10.1159/000341631 | Intervention/exposure
180 | Olsson K, González-Padilla E, Janzi S, et al. Clusters of carbohydrate-rich foods and associations with type 2 diabetes incidence: a prospective cohort study. Nutr J. 2023;22(1):71. doi:10.1186/s12937-023-00906-0 | Intervention/exposure
181 | Palatini P, Benetti E, Mos L, et al. Association of coffee consumption and CYP1A2 polymorphism with risk of impaired fasting glucose in hypertensive patients. Eur J Epidemiol. 2015;30(3):209-217. doi:10.1007/s10654-015-9990-z | Intervention/exposure
182 | Papier K, D’Este C, Bain C, et al. Consumption of sugar-sweetened beverages and type 2 diabetes incidence in Thai adults: results from an 8-year prospective study. Nutr Diabetes. 2017;7(6):e283. doi:10.1038/nutd.2017.27 | Country
183 | Parnell LD, Noel SE, Bhupathiraju SN, et al. Metabolite patterns link diet, obesity, and type 2 diabetes in a Hispanic population. Metabolomics. 2021;17(10):88. doi:10.1007/s11306-021-01835-x | Intervention/exposure
184 | Pereira MA, Jacobs DR Jr, Van Horn L, Slattery ML, Kartashov AI, Ludwig DS. Dairy consumption, obesity, and the insulin resistance syndrome in young adults: the CARDIA Study. JAMA. 2002;287(16):2081-2089. doi:10.1001/jama.287.16.2081 | Intervention/exposure
185 | Pereira MA, Parker ED, Folsom AR. Coffee consumption and risk of type 2 diabetes mellitus: an 11-year prospective study of 28 812 postmenopausal women. Arch Intern Med. 2006;166(12):1311-1316. doi:10.1001/archinte.166.12.1311 | Intervention/exposure
186 | Perelli L, Alcaraz A, Vianna CMM, et al. Health and economic burden of sugarsweetened beverages consumption in Brazil. Cad Saude Publica. 2023;39(12):e00249422. doi:10.1590/0102-311XEN249422 | Study design
187 | Platt DE, Ghassibe-Sabbagh M, Salameh P, et al. Caffeine Impact on Metabolic Syndrome Components Is Modulated by a CYP1A2 Variant. Ann Nutr Metab. 2016;68(1):1-11. doi:10.1159/000441481 | Study design
188 | Ponce O, Benassi R, Cesar T. Orange juice associated with a balanced diet mitigated risk factors of metabolic syndrome: A randomized controlled trial. J Nutr Intermed Metab. 2019;17:100101. doi:10.1016/j.jnim.2019.100101 | Intervention/exposure
189 | Rezvani R, Cianflone K, McGahan JP, et al. Effects of sugar-sweetened beverages on plasma acylation stimulating protein, leptin and adiponectin: relationships with metabolic outcomes. Obesity (Silver Spring). 2013;21(12):2471-2480. doi:10.1002/oby.20437 | Intervention/exposure
190 | Ribeiro C, Dourado G, Cesar T. Orange juice allied to a reduced-calorie diet results in weight loss and ameliorates obesity-related biomarkers: A randomized controlled trial. Nutrition. 2017;38:13-19. doi:10.1016/j.nut.2016.12.020 | Intervention/exposure
191 | Rivera-Paredez B, Torres-Ibarra L, González-Morales R, et al. Cumulative soft drink consumption is associated with insulin resistance in Mexican adults. Am J Clin Nutr. 2020;112(3):661-668. doi:10.1093/ajcn/nqaa169 | Outcome
192 | Rosado JL, Garcia OP, Ronquillo D, et al. Intake of milk with added micronutrients increases the effectiveness of an energy-restricted diet to reduce body weight: a randomized controlled clinical trial in Mexican women. J Am Diet Assoc. 2011;111(10):1507-1516. doi:10.1016/j.jada.2011.07.011 | Intervention/exposure
193 | Rosengren A, Dotevall A, Wilhelmsen L, Thelle D, Johansson S. Coffee and incidence of diabetes in Swedish women: a prospective 18-year follow-up study. J Intern Med. 2004;255(1):89-95. doi:10.1046/j.1365-2796.2003.01260.x | Intervention/exposure
194 | Sá CM, Ramos AA, Azevedo MF, Lima CF, Fernandes-Ferreira M, Pereira-Wilson C. Sage tea drinking improves lipid profile and antioxidant defences in humans. Int J Mol Sci. 2009;10(9):3937-3950. doi:10.3390/ijms10093937 | Study design
195 | Said MA, van de Vegte YJ, Verweij N, van der Harst P. Associations of Observational and Genetically Determined Caffeine Intake With Coronary Artery Disease and Diabetes Mellitus. J Am Heart Assoc. 2020;9(24):e016808. doi:10.1161/JAHA.120.016808 | Intervention/exposure
196 | Salazar-Martinez E, Willett WC, Ascherio A, et al. Coffee consumption and risk for type 2 diabetes mellitus. Ann Intern Med. 2004;140(1):1-8. doi:10.7326/0003-4819-140-1200401060-00005 | Intervention/exposure
197 | Samara A, Herbeth B, Ndiaye NC, et al. Dairy product consumption, calcium intakes, and metabolic syndrome-related factors over 5 years in the STANISLAS study. Nutrition. 2013;29(3):519-524. doi:10.1016/j.nut.2012.08.013 | Intervention/exposure
198 | Sarriá B, Martínez-López S, Sierra-Cinos JL, García-Diz L, Mateos R, Bravo-Clemente L. Regularly consuming a green/roasted coffee blend reduces the risk of metabolic syndrome. Eur J Nutr. 2018;57(1):269-278. doi:10.1007/s00394-016-1316-8 | Comparator
199 | Sarriá B, Sierra-Cinos JL, García-Diz L, Martínez-López S, Mateos R, Bravo-Clemente L. Green/Roasted Coffee May Reduce Cardiovascular Risk in Hypercholesterolemic Subjects by Decreasing Body Weight, Abdominal Adiposity and Blood Pressure. Foods. 2020;9(9):1191. doi:10.3390/foods9091191 | Other (e.g., duplicative data)
200 | Sartorelli DS, Fagherazzi G, Balkau B, et al. Differential effects of coffee on the risk of type 2 diabetes according to meal consumption in a French cohort of women: the E3N/EPIC cohort study. Am J Clin Nutr. 2010;91(4):1002-1012. doi:10.3945/ajcn.2009.28741 | Intervention/exposure
201 | Scheffers FR, Boer JM, Wijga AH, van der Schouw YT, Smit HA, Verschuren WM. Substitution of pure fruit juice for fruit and sugar-sweetened beverages and cardiometabolic risk in European Prospective Investigation into Cancer and Nutrition (EPIC)-NL: a prospective cohort study. Public Health Nutr. 2022;25(6):1504-1514. doi:10.1017/S1368980021000914 | Intervention/exposure
202 | Scheffers FR, Wijga AH, Verschuren WMM, et al. Pure Fruit Juice and Fruit Consumption Are Not Associated with Incidence of Type 2 Diabetes after Adjustment for Overall Dietary Quality in the European Prospective Investigation into Cancer and Nutrition-Netherlands (EPIC-NL) Study. J Nutr. 2020;150(6):1470-1477. doi:10.1093/jn/nxz340 | Intervention/exposure
203 | Schmidt KA, Cromer G, Burhans MS, et al. The impact of diets rich in low-fat or full-fat dairy on glucose tolerance and its determinants: a randomized controlled trial. Am J Clin Nutr. 2021;113(3):534-547. doi:10.1093/ajcn/nqaa301 | Intervention/exposure
204 | Schoppen S, Pérez-Granados AM, Carbajal A, et al. A sodium-rich carbonated mineral water reduces cardiovascular risk in postmenopausal women. J Nutr. 2004;134(5):1058-1063. doi:10.1093/jn/134.5.1058 | Study design
205 | Schulze MB, Hoffmann K, Boeing H, et al. An accurate risk score based on anthropometric, dietary, and lifestyle factors to predict the development of type 2 diabetes. Diabetes Care. 2007;30(3):510-515. doi:10.2337/dc06-2089 | Study design
206 | Scott C, Au-Yeung F, Strom N, et al. PTFS08-02-23 Comparison of a Daily Stevia Beverage vs. a Sucrose Sweetened Beverage on the Human Gut Microbiome, Cardiometabolic Functions and Anthropometric Measurements. Curr Dev Nutr. 2023;7:S1. doi:10.1016/j.cdnut.2023.101447 | Publication status
207 | Shenoy SF, Poston WS, Reeves RS, et al. Weight loss in individuals with metabolic syndrome given DASH diet counseling when provided a low sodium vegetable juice: a randomized controlled trial. Nutr J. 2010;9:8. doi:10.1186/1475-2891-9-8 | Intervention/exposure
208 | Shi L, Brunius C, Johansson I, et al. Plasma metabolite biomarkers of boiled and filtered coffee intake and their association with type 2 diabetes risk. J Intern Med. 2020;287(4):405-421. doi:10.1111/joim.13009 | Comparator
209 | Shin H, Yoon YS, Lee Y, Kim CI, Oh SW. Dairy product intake is inversely associated with metabolic syndrome in Korean adults: Anseong and Ansan cohort of the Korean Genome and Epidemiology Study. J Korean Med Sci. 2013;28(10):1482-1488. doi:10.3346/jkms.2013.28.10.1482 | Intervention/exposure
210 | Simão TN, Lozovoy MA, Simão AN, et al. Reduced-energy cranberry juice increases folic acid and adiponectin and reduces homocysteine and oxidative stress in patients with the metabolic syndrome. Br J Nutr. 2013;110(10):1885-1894. doi:10.1017/S0007114513001207 | Outcome
211 | Siqueira JH, Pereira TSS, Moreira AD, et al. Consumption of sugar-sweetened soft drinks and risk of metabolic syndrome and its components: results of the ELSA-Brasil study (2008-2010 and 2012-2014). J Endocrinol Invest. 2023;46(1):159-171. doi:10.1007/s40618-022-01895-3 | Outcome
212 | Sluijs I, Forouhi NG, Beulens JW, et al. The amount and type of dairy product intake and incident type 2 diabetes: results from the EPIC-InterAct Study. Am J Clin Nutr. 2012;96(2):382-390. doi:10.3945/ajcn.111.021907 | Intervention/exposure
213 | Sluijs I, Forouhi NG, Beulens JW, et al. The amount and type of dairy product intake and incident type 2 diabetes: results from the EPIC-InterAct Study. Am J Clin Nutr. 2012;96(2):382-390. doi:10.3945/ajcn.111.021907 | Duplicate
214 | Slurink IA, Chen L, Magliano DJ, Kupper N, Smeets T, Soedamah-Muthu SS. Dairy Product Consumption and Incident Prediabetes in the Australian Diabetes, Obesity, and Lifestyle Study With 12 Years of Follow-Up. J Nutr. 2023;153(6):1742-1752. doi:10.1016/j.tjnut.2023.03.032 | Intervention/exposure
215 | Slurink IA, Corpeleijn E, Bakker SJ, et al. Dairy consumption and incident prediabetes: prospective associations and network models in the large population-based Lifelines Study. Am J Clin Nutr. 2023;118(6):1077-1090. doi:10.1016/j.ajcnut.2023.10.002 | Intervention/exposure
216 | Slurink IA, Corpeleijn E, Bakker SJ, et al. Dairy consumption and incident prediabetes: prospective associations and network models in the large population-based Lifelines Study. Am J Clin Nutr. 2023;118(6):1077-1090. doi:10.1016/j.ajcnut.2023.10.002 | Duplicate
217 | Slurink IAL, den Braver NR, Rutters F, et al. Dairy product consumption and incident prediabetes in Dutch middle-aged adults: the Hoorn Studies prospective cohort. Eur J Nutr. 2022;61(1):183-196. doi:10.1007/s00394-021-02626-9 | Intervention/exposure
218 | Slurink IAL, Voortman T, Ochoa-Rosales C, et al. Dairy Product Consumption in Relation to Incident Prediabetes and Longitudinal Insulin Resistance in the Rotterdam Study. Nutrients. 2022;14(3):415. doi:10.3390/nu14030415 | Intervention/exposure
219 | Smith B, Wingard DL, Smith TC, Kritz-Silverstein D, Barrett-Connor E. Does coffee consumption reduce the risk of type 2 diabetes in individuals with impaired glucose?. Diabetes Care. 2006;29(11):2385-2390. doi:10.2337/dc06-1084 | Intervention/exposure
220 | Soedamah-Muthu SS, Masset G, Verberne L, Geleijnse JM, Brunner EJ. Consumption of dairy products and associations with incident diabetes, CHD and mortality in the Whitehall II study. Br J Nutr. 2013;109(4):718-726. doi:10.1017/S0007114512001845 | Intervention/exposure
221 | Song Y, Manson JE, Buring JE, Sesso HD, Liu S. Associations of dietary flavonoids with risk of type 2 diabetes, and markers of insulin resistance and systemic inflammation in women: a prospective study and cross-sectional analysis. J Am Coll Nutr. 2005;24(5):376-384. doi:10.1080/07315724.2005.10719488 | Intervention/exposure
222 | Stanhope KL, Schwarz JM, Keim NL, et al. Consuming fructose-sweetened, not glucose-sweetened, beverages increases visceral adiposity and lipids and decreases insulin sensitivity in overweight/obese humans. J Clin Invest. 2009;119(5):1322-1334. doi:10.1172/JCI37385 | Intervention/exposure
223 | St-Onge MP, Goree LL, Gower B. High-milk supplementation with healthy diet counseling does not affect weight loss but ameliorates insulin action compared with lowmilk supplementation in overweight children. J Nutr. 2009;139(5):933-938. doi:10.3945/jn.108.102079 | Comparator
224 | Struijk EA, Heraclides A, Witte DR, et al. Dairy product intake in relation to glucose regulation indices and risk of type 2 diabetes. Nutr Metab Cardiovasc Dis. 2013;23(9):822-828. doi:10.1016/j.numecd.2012.05.011 | Intervention/exposure
225 | Stuber JM, Vissers LET, Verschuren WMM, Boer JMA, van der Schouw YT, Sluijs I. Substitution among milk and yogurt products and the risk of incident type 2 diabetes in the EPIC-NL cohort. J Hum Nutr Diet. 2021;34(1):54-63. doi:10.1111/jhn.12767 | Intervention/exposure
226 | Swarbrick MM, Stanhope KL, Elliott SS, et al. Consumption of fructose-sweetened beverages for 10 weeks increases postprandial triacylglycerol and apolipoprotein-B concentrations in overweight and obese women. Br J Nutr. 2008;100(5):947-952. doi:10.1017/S0007114508968252 | Intervention/exposure
227 | Taba N, Valge HK, Metspalu A, et al. Mendelian Randomization Identifies the Potential Causal Impact of Dietary Patterns on Circulating Blood Metabolites. Front Genet. 2021;12:738265. doi:10.3389/fgene.2021.738265 | Outcome
228 | Talaei M, Pan A, Yuan JM, Koh WP. Dairy intake and risk of type 2 diabetes. Clin Nutr. 2018;37(2):712-718. doi:10.1016/j.clnu.2017.02.022 | Intervention/exposure
229 | Tan LJ, Jeon HJ, Park S, et al. Association of Coffee Consumption and Its Types According to Addition of Sugar and Creamer with Metabolic Syndrome Incidence in a Korean Population from the Health Examinees (HEXA) Study. Nutrients. 2021;13(3):920. doi:10.3390/nu13030920 | Intervention/exposure
230 | Tanaka S, Uenishi K, Ishida, et al. A randomized intervention trial of 24-wk dairy consumption on waist circumference, blood pressure, and fasting blood sugar and lipids in Japanese men with metabolic syndrome. J Nutr Sci Vitaminol (Tokyo). 2014. 60:30512. doi:10.3177/jnsv.60.305. | Intervention/exposure
231 | Tate DF, Turner-McGrievy G, Stevens J, et al. Replacing caloric beverages with water or diet beverages for weight loss in adults: results of a 6-month randomized controlled trial. Obesity (Silver Spring). 2011;19:S68. doi:10.1038/oby.2011.222 | Publication status
232 | Tehrani HG, Allahdadian M, Zarre F, Ranjbar H, Allahdadian F. Effect of green tea on metabolic and hormonal aspect of polycystic ovarian syndrome in overweight and obese women suffering from polycystic ovarian syndrome: A clinical trial. J Educ Health Promot. 2017;6:36. doi:10.4103/jehp.jehp_67_15 | Intervention/exposure
233 | Toolsee NA, Aruoma OI, Gunness TK, et al. Effectiveness of green tea in a randomized human cohort: relevance to diabetes and its complications. Biomed Res Int. 2013;2013:412379. doi:10.1155/2013/412379 | Intervention/exposure
234 | Toxqui L, Vaquero MP. An Intervention with Mineral Water Decreases Cardiometabolic Risk Biomarkers. A Crossover, Randomised, Controlled Trial with Two Mineral Waters in Moderately Hypercholesterolaemic Adults. Nutrients. 2016;8(7):400. doi:10.3390/nu8070400 | Comparator
235 | Trapp G, Hurworth M, Jacoby P, et al. Energy drink intake and metabolic syndrome: A prospective investigation in young adults. Nutr Metab Cardiovasc Dis. 2020;30(10):1679-1684. doi:10.1016/j.numecd.2020.06.012 | Intervention/exposure
236 | Trichia E, Koulman A, Stewart ID, et al. Plasma Metabolites Related to the Consumption of Different Types of Dairy Products and Their Association with New-Onset Type 2 Diabetes: Analyses in the Fenland and EPIC-Norfolk Studies, United Kingdom. Mol Nutr Food Res. 2024;68(1):e2300154. doi:10.1002/mnfr.202300154 | Intervention/exposure
237 | Trichia E, Luben R, Khaw KT, Wareham NJ, Imamura F, Forouhi NG. The associations of longitudinal changes in consumption of total and types of dairy products and markers of metabolic risk and adiposity: findings from the European Investigation into Cancer and Nutrition (EPIC)-Norfolk study, United Kingdom. Am J Clin Nutr. 2020;111(5):10181026. doi:10.1093/ajcn/nqz335 | Intervention/exposure
238 | Tsai KZ, Huang WC, Sui X, Lavie CJ, Lin GM. Moderate or greater daily coffee consumption is associated with lower incidence of metabolic syndrome in Taiwanese militaries: results from the CHIEF cohort study. Front Nutr. 2023;10:1321916. doi:10.3389/fnut.2023.1321916 | Intervention/exposure
239 | Tsang C, Smail NF, Almoosawi S, Davidson I, Al-Dujaili EA. Intake of polyphenol-rich pomegranate pure juice influences urinary glucocorticoids, blood pressure and homeostasis model assessment of insulin resistance in human volunteers. J Nutr Sci. 2012;1:e9. doi:10.1017/jns.2012.10 | Comparator
240 | Tsitsimpikou C, Tsarouhas K, Kioukia-Fougia N, et al. Dietary supplementation with tomato-juice in patients with metabolic syndrome: a suggestion to alleviate detrimental clinical factors. Food Chem Toxicol. 2014;74:9-13. doi:10.1016/j.fct.2014.08.014 | Intervention/exposure
241 | Tuomilehto J, Hu G, Bidel S, Lindström J, Jousilahti P. Coffee consumption and risk of type 2 diabetes mellitus among middle-aged Finnish men and women. JAMA. 2004;291(10):1213-1219. doi:10.1001/jama.291.10.1213 | Intervention/exposure
242 | van Dam RM, Dekker JM, Nijpels G, et al. Coffee consumption and incidence of impaired fasting glucose, impaired glucose tolerance, and type 2 diabetes: the Hoorn Study. Diabetologia. 2004;47(12):2152-2159. doi:10.1007/s00125-004-1573-6 | Intervention/exposure
243 | van Dam RM, Feskens EJ. Coffee consumption and risk of type 2 diabetes mellitus. Lancet. 2002;360(9344):1477-1478. doi:10.1016/S0140-6736(02)11436-X | Intervention/exposure
244 | van Dam RM, Pasman WJ, Verhoef P. Effects of coffee consumption on fasting blood glucose and insulin concentrations: randomized controlled trials in healthy volunteers. Diabetes Care. 2004;27(12):2990-2992. doi:10.2337/diacare.27.12.2990 | Intervention/exposure
245 | van Dam RM, Willett WC, Manson JE, Hu FB. Coffee, caffeine, and risk of type 2 diabetes: a prospective cohort study in younger and middle-aged U.S. women. Diabetes Care. 2006;29(2):398-403. doi:10.2337/diacare.29.02.06.dc05-1512 | Intervention/exposure
246 | van Dieren S, Uiterwaal CS, van der Schouw, et al. Coffee and tea consumption and risk of type 2 diabetes. Diabetologia. 2009;52:2561-9. doi:10.1007/s00125-009-1516-3. | Intervention/exposure
247 | Van Hulst A, Ybarra M, Mathieu ME, Benedetti A, Paradis G, Henderson M. Determinants of new onset cardiometabolic risk among normal weight children. Int J Obes (Lond). 2020;44(4):781-789. doi:10.1038/s41366-019-0483-0 | Outcome
248 | van ’t Riet E, Dekker JM, Sun Q, Nijpels G, Hu FB, van Dam RM. Role of adiposity and lifestyle in the relationship between family history of diabetes and 20-year incidence of type 2 diabetes in U.S. women. Diabetes Care. 2010;33(4):763-767. doi:10.2337/dc09-1586 | Intervention/exposure
249 | van Woudenbergh GJ, Kuijsten A, et al. Tea consumption and incidence of type 2 diabetes in Europe: the EPIC-InterAct case-cohort study. PLoS One. 2012;7(5):e36910. doi:10.1371/journal.pone.0036910 | Intervention/exposure
250 | Ventura AK, Loken E, Birch LL. Risk profiles for metabolic syndrome in a nonclinical sample of adolescent girls. Pediatrics. 2006;118(6):2434-2442. doi:10.1542/peds.20061527 | Outcome
251 | Vieira Senger AE, Schwanke CH, Gomes I, Valle Gottlieb MG. Effect of green tea (Camellia sinensis) consumption on the components of metabolic syndrome in elderly. J Nutr Health Aging. 2012;16(9):738-742. doi:10.1007/s12603-012-0081-5 | Intervention/exposure
252 | Villegas R, Gao YT, Dai Q, et al. Dietary calcium and magnesium intakes and the risk of type 2 diabetes: the Shanghai Women’s Health Study. Am J Clin Nutr. 2009;89(4):1059-1067. doi:10.3945/ajcn.2008.27182 | Intervention/exposure
253 | Villegas R, Gao YT, Yang G, et al. Legume and soy food intake and the incidence of type 2 diabetes in the Shanghai Women’s Health Study. Am J Clin Nutr. 2008;87(1):162-167. doi:10.1093/ajcn/87.1.162 | Country
254 | Villegas R, Yang G, Gao YT, et al. Dietary patterns are associated with lower incidence of type 2 diabetes in middle-aged women: the Shanghai Women’s Health Study. Int J Epidemiol. 2010;39(3):889-899. doi:10.1093/ije/dyq008 | Intervention/exposure
255 | Vimaleswaran KS, Zhou A, Cavadino A, Hyppönen E. Evidence for a causal association between milk intake and cardiometabolic disease outcomes using a two-sample Mendelian Randomization analysis in up to 1,904,220 individuals. Int J Obes (Lond). 2021;45(8):1751-1762. doi:10.1038/s41366-021-00841-2 | Intervention/exposure
256 | Vissers LET, Sluijs I, van der Schouw YT, et al. Dairy Product Intake and Risk of Type 2 Diabetes in EPIC-InterAct: A Mendelian Randomization Study. Diabetes Care. 2019;42(4):568-575. doi:10.2337/dc18-2034 | Intervention/exposure
257 | Voortman T, Kiefte-de Jong JC, Ikram MA, et al. Adherence to the 2015 Dutch dietary guidelines and risk of non-communicable diseases and mortality in the Rotterdam Study. Eur J Epidemiol. 2017;32(11):993-1005. doi:10.1007/s10654-017-0295-2 | Intervention/exposure
258 | Wang J, Light K, Henderson M, et al. Consumption of added sugars from liquid but not solid sources predicts impaired glucose homeostasis and insulin resistance among youth at risk of obesity. J Nutr. 2014;144(1):81-86. doi:10.3945/jn.113.182519 | Intervention/exposure
259 | Wang X, Jia J, Huang T. Coffee Types and Type 2 Diabetes Mellitus: Large-Scale Cross-Phenotype Association Study and Mendelian Randomization Analysis. Front Endocrinol (Lausanne). 2022;13:818831. doi:10.3389/fendo.2022.818831 | Intervention/exposure
260 | Wedick NM, Brennan AM, Sun Q, Hu FB, Mantzoros CS, van Dam RM. Effects of caffeinated and decaffeinated coffee on biological risk factors for type 2 diabetes: a randomized controlled trial. Nutr J. 2011;10:93. doi:10.1186/1475-2891-10-93 | Intervention/exposure
261 | Wedick NM, Pan A, Cassidy A, et al. Dietary flavonoid intakes and risk of type 2 diabetes in US men and women. Am J Clin Nutr. 2012;95(4):925-933. doi:10.3945/ajcn.111.028894 | Intervention/exposure
262 | Wennersberg MH, Smedman A, Turpeinen AM, et al. Dairy products and metabolic effects in overweight men and women: results from a 6-mo intervention study. Am J Clin Nutr. 2009;90(4):960-968. doi:10.3945/ajcn.2009.27664 | Intervention/exposure
263 | Wong THT, Burlutsky G, Gopinath B, Flood VM, Mitchell P, Louie JCY. The longitudinal association between coffee and tea consumption and the risk of metabolic syndrome and its component conditions in an older adult population. J Nutr Sci. 2022;11:e79. doi:10.1017/jns.2022.78 | Intervention/exposure
264 | Wuni R, Lakshmipriya N, Abirami K, et al. Higher Intake of Dairy Is Associated with Lower Cardiometabolic Risks and Metabolic Syndrome in Asian Indians. Nutrients. 2022;14(18):3699. doi:10.3390/nu14183699 | Country
265 | Yang H, Kim H, Kim JM, Chung HW, Chang N. Associations of dietary intake and metabolic syndrome risk parameters in Vietnamese female marriage immigrants in South Korea: The KoGES follow-up study. Nutr Res Pract. 2016;10(3):313-320. doi:10.4162/nrp.2016.10.3.313 | Intervention/exposure
266 | Yang J, Tobias DK, Li S, et al. Habitual coffee consumption and subsequent risk of type 2 diabetes in individuals with a history of gestational diabetes - a prospective study. Am J Clin Nutr. 2022;116(6):1693-1703. doi:10.1093/ajcn/nqac241 | Health status
267 | Yang Q, Lin SL, Au Yeung SL, et al. Genetically predicted milk consumption and bone health, ischemic heart disease and type 2 diabetes: a Mendelian randomization study. Eur J Clin Nutr. 2017;71(8):1008-1012. doi:10.1038/ejcn.2017.8 | Intervention/exposure
268 | Ye S, Chen H, Ren X, et al. Carbonated beverage consumption is associated with lower C-peptide in adolescents. J Pediatr Endocrinol Metab. 2019;32(5):447-454. doi:10.1515/jpem-2018-0286 | Study design
269 | Yeates AJ, Gilmartin N, O’Kane SM, Pourshahidi LK, Mulhern MS, Strain JJ. The effect of cow’s milk consumption on cardiometabolic health in women of childbearing age. Proc Nutr Soc. 2017;76(OCE3):E58. doi:10.1017/S0029665117001318 | Publication status
270 | Yu S, Wang B, Li G, Guo X, Yang H, Sun Y. Habitual Tea Consumption Increases the Incidence of Metabolic Syndrome in Middle-Aged and Older Individuals. Nutrients. 2023;15(6):1448. doi:10.3390/nu15061448 | Intervention/exposure
271 | Yuan S, Sun J, Lu Y, et al. Health effects of milk consumption: phenome-wide Mendelian randomization study. BMC Med. 2022;20(1):455. doi:10.1186/s12916-022-02658-w | Intervention/exposure
272 | Yuan S, Larsson SC. An atlas on risk factors for type 2 diabetes: a wide-angled Mendelian randomisation study. Diabetologia. 2020;63(11):2359-2371. doi:10.1007/s00125-020-05253-x | Intervention/exposure
273 | Yun H, Sun L, Wu Q, et al. Lipidomic Signatures of Dairy Consumption and Associated Changes in Blood Pressure and Other Cardiovascular Risk Factors Among Chinese Adults. Hypertension. 2022;79(8):1617-1628. doi:10.1161/HYPERTENSIONAHA.122.18981 | Country
274 | Yuzbashian E, Pakseresht M, Vena J, Chan CB. Association of dairy consumption patterns with the incidence of type 2 diabetes: Findings from Alberta’s Tomorrow Project. Nutr Metab Cardiovasc Dis. 2022;32(12):2760-2771. doi:10.1016/j.numecd.2022.09.022 | Duplicate
275 | Yuzbashian E, Asghari G, Mirmiran P, Chan CB, Azizi F. Changes in dairy product consumption and subsequent type 2 diabetes among individuals with prediabetes: Tehran Lipid and Glucose Study. Nutr J. 2021;20(1):88. doi:10.1186/s12937-02100745-x | Intervention/exposure
276 | Yuzbashian E, Nosrati-Oskouie M, Asghari G, Chan CB, Mirmiran P, Azizi F. Associations of dairy intake with risk of incident metabolic syndrome in children and adolescents: Tehran Lipid and Glucose Study. Acta Diabetol. 2021;58(4):447-457. doi:10.1007/s00592-020-01651-0 | Intervention/exposure
277 | Zair Y, Kasbi-Chadli F, Housez B, et al. Effect of a high bicarbonate mineral water on fasting and postprandial lipemia in moderately hypercholesterolemic subjects: a pilot study. Lipids Health Dis. 2013;12:105. doi:10.1186/1476-511X-12-105 | Comparator
278 | Zhang S, Meng G, Zhang Q, et al. Dairy intake and risk of type 2 diabetes: results of a large prospective cohort. Food Funct. 2023;14(21):9695-9706. doi:10.1039/d3fo02023a | Intervention/exposure
279 | Zhang Y, Bian Z, Lu H, Wang L, Xu J, Wang C. Association between tea consumption and glucose metabolism and insulin secretion in the Shanghai High-risk Diabetic Screen (SHiDS) study. BMJ Open Diabetes Res Care. 2023;11(2):e003266. doi:10.1136/bmjdrc-2022-003266 | Study design
280 | Zhang Y, Lee ET, Cowan LD, Fabsitz RR, Howard BV. Coffee consumption and the incidence of type 2 diabetes in men and women with normal glucose tolerance: the Strong Heart Study. Nutr Metab Cardiovasc Dis. 2011;21(6):418-423. doi:10.1016/j.numecd.2009.10.020 | Intervention/exposure
281 | Zhang Y, Wang R, Tang X, et al. A Mendelian Randomization Study of the Effect of Tea Intake on Type 2 Diabetes. Front Genet. 2022;13:835917. doi:10.3389/fgene.2022.835917 | Intervention/exposure