# References for Articles Included in the Systematic Review

1 Aljahdali AA, Peterson KE, Cantoral A, . Diet Quality Scores and Cardiometabolic Risk Factors in Mexican Children and Adolescents: A Longitudinal Analysis. Nutrients. Feb 20 2022;14(4)doi:10.3390/nu14040896
2 Asghari G, Yuzbashian E, Mirmiran P, Hooshmand F, Najafi R, Azizi F. Dietary Approaches to Stop Hypertension (DASH) Dietary Pattern Is Associated with Reduced Incidence of Metabolic Syndrome in Children and Adolescents. J Pediatr. Jul 2016;174:178–184 e1. doi:10.1016/j.jpeds.2016.03.077 27156186
3 Buckland G, Taylor CM, Emmett PM, Johnson L, Northstone K. Prospective association between a Mediterranean-style dietary score in childhood and cardiometabolic risk in young adults from the ALSPAC birth cohort. Eur J Nutr. Mar 2022;61(2):737–752. doi:10.1007/s00394-021-02652-7 34532761
4 Bull CJ, Northstone K. Childhood dietary patterns and cardiovascular risk factors in adolescence: results from the Avon Longitudinal Study of Parents and Children (ALSPAC) cohort. Public Health Nutr. Dec 2016;19(18):3369–3377. doi:10.1017/S1368980016001592 27339189
5 Chan She Ping-Delfos WL, Beilin LJ, Oddy WH, Burrows S, Mori TA. Use of the Dietary Guideline Index to assess cardiometabolic risk in adolescents. Br J Nutr. Jun 14 2015;113(11):1741–52. doi:10.1017/S0007114515001026 25873301
6 Cosier D, Charlton K, Schoenaker D. The association between dietary trajectories across childhood and blood pressure in early adolescence: The Longitudinal Study of Australian Children. Eur J Clin Nutr. Jun 2023;77(6):677–683. doi:10.1038/s41430-023-01274-y 36797490
7 Costa JP, Magalhaes V, Araujo J, Ramos E. A lower energy intake contributes to a better cardiometabolic profile in adolescence: Data from the EPITeen cohort. Nutr Res. Mar 2023;111:14–23. doi:10.1016/j.nutres.2023.01.002 36791661
8 Dahm CC, Chomistek AK, Jakobsen MU, . Adolescent Diet Quality and Cardiovascular Disease Risk Factors and Incident Cardiovascular Disease in Middle-Aged Women. J Am Heart Assoc. Dec 20 2016;5(12)doi:10.1161/JAHA.116.003583
9 Farhadnejad H, Asghari G, Mirmiran P, Azizi F. Dietary approach to stop hypertension diet and cardiovascular risk factors among 10- to 18-year-old individuals. Pediatr Obes. Apr 2018;13(4):185–194. doi:10.1111/ijpo.12268 29363277
10 Kerr JA, Liu RS, Gasser CE, . Diet quality trajectories and cardiovascular phenotypes/metabolic syndrome risk by 11-12 years. Int J Obes (Lond). Jul 2021;45(7):1392–1403. doi:10.1038/s41366-021-00800-x 33824404
11 Krijger JA, Nicolaou M, Nguyen AN, Voortman T, Hutten BA, Vrijkotte TG. Diet quality at age 5-6 and cardiovascular outcomes in preadolescents. Clin Nutr ESPEN. Jun 2021;43:506–513. doi:10.1016/j.clnesp.2021.02.011 34024563
12 Leffa PS, Hoffman DJ, Rauber F, Sangalli CN, Valmorbida JL, Vitolo MR. Longitudinal associations between ultra-processed foods and blood lipids in childhood. Br J Nutr. Aug 14 2020;124(3):341–348. doi:10.1017/S0007114520001233 32248849
13 Luque V, Closa-Monasterolo R, Grote V, . Dietary patterns acquired in early life are associated with cardiometabolic markers at school age. Clin Nutr. Jul 2021;40(7):4606–4614. doi:10.1016/j.clnu.2021.06.001 34229265
14 McCourt HJ, Draffin CR, Woodside JV, . Dietary patterns and cardiovascular risk factors in adolescents and young adults: the Northern Ireland Young Hearts Project. Br J Nutr. Nov 28 2014;112(10):1685–98. doi:10.1017/S0007114514002682 25234582
15 Montejano Vallejo R, Schulz CA, van de Locht K, Oluwagbemigun K, Alexy U, Nothlings U. Associations of Adherence to a Dietary Index Based on the EAT-Lancet Reference Diet with Nutritional, Anthropometric, and Ecological Sustainability Parameters: Results from the German DONALD Cohort Study. J Nutr. Jul 6 2022;152(7):1763–1772. doi:10.1093/jn/nxac094 35554563
16 Pinto A, Santos AC, Lopes C, Oliveira A. Dietary patterns at 7 year-old and their association with cardiometabolic health at 10 year-old. Clin Nutr. Apr 2020;39(4):1195–1202. doi:10.1016/j.clnu.2019.05.007 31133488
17 Rauber F, Campagnolo PD, Hoffman DJ, Vitolo MR. Consumption of ultra-processed food products and its effects on children’s lipid profiles: a longitudinal study. Nutr Metab Cardiovasc Dis. Jan 2015;25(1):116–22. doi:10.1016/j.numecd.2014.08.001 25240690
18 Siddiqui NZ, Nguyen AN, Santos S, Voortman T. Diet quality and cardiometabolic health in childhood: the Generation R Study. Eur J Nutr. Mar 2022;61(2):729–736. doi:10.1007/s00394-021-02673-2 34528119
19 Asoudeh F, Fallah M, Aminianfar A, . The effect of Mediterranean diet on inflammatory biomarkers and components of metabolic syndrome in adolescent girls. J Endocrinol Invest. Oct 2023;46(10):1995–2004. doi:10.1007/s40618-023-02027-1 36795242
20 Agha G, Loucks EB, Tinker LF, . Healthy lifestyle and decreasing risk of heart failure in women: the Women’s Health Initiative observational study. J Am Coll Cardiol. Oct 28 2014;64(17):1777–85. doi:10.1016/j.jacc.2014.07.981 25443698
21 Ahmad S, Moorthy MV, Demler OV, . Assessment of Risk Factors and Biomarkers Associated With Risk of Cardiovascular Disease Among Women Consuming a Mediterranean Diet. JAMA Netw Open. Dec 7 2018;1(8):e185708. doi:10.1001/jamanetworkopen.2018.5708 30646282
22 Aigner A, Becher H, Jacobs S, . Low diet quality and the risk of stroke mortality: the multiethnic cohort study. Eur J Clin Nutr. Jul 2018;72(7):1035–1045. doi:10.1038/s41430-018-0103-4 29426930
23 Baden MY, Liu G, Satija A, . Changes in Plant-Based Diet Quality and Total and Cause-Specific Mortality. Circulation. Sep 17 2019;140(12):979–991. doi:10.1161/CIRCULATIONAHA.119.041014 31401846
24 Baden MY, Shan Z, Wang F, . Quality of Plant-Based Diet and Risk of Total, Ischemic, and Hemorrhagic Stroke. Neurology. Apr 13 2021;96(15):e1940–e1953. doi:10.1212/WNL.0000000000011713 33692165
25 Bertoia ML, Triche EW, Michaud DS, . Mediterranean and Dietary Approaches to Stop Hypertension dietary patterns and risk of sudden cardiac death in postmenopausal women. Am J Clin Nutr. Feb 2014;99(2):344–51. doi:10.3945/ajcn.112.056135 24351877
26 Bhupathiraju SN, Sawicki CM, Goon S, . A healthy plant-based diet is favorably associated with cardiometabolic risk factors among participants of South Asian ancestry. Am J Clin Nutr. Oct 6 2022;116(4):1078–1090. doi:10.1093/ajcn/nqac174 35731596
27 Booth JN, 3rd, Colantonio LD, Howard G, . Healthy lifestyle factors and incident heart disease and mortality in candidates for primary prevention with statin therapy. Int J Cardiol. Mar 15 2016;207:196–202. doi:10.1016/j.ijcard.2016.01.001 26803243
28 Campos CL, Wood A, Burke GL, Bahrami H, Bertoni AG. Dietary Approaches to Stop Hypertension Diet Concordance and Incident Heart Failure: The Multi-Ethnic Study of Atherosclerosis. Am J Prev Med. Jun 2019;56(6):819–826. doi:10.1016/j.amepre.2018.11.022 31003810
29 Chang RS, Xu M, Brown SH, . Relation of the Dietary Approaches to Stop Hypertension Dietary Pattern to Heart Failure Risk and Socioeconomic Status (from the Southern Community Cohort Study). Am J Cardiol. Apr 15 2022;169:71–77. doi:10.1016/j.amjcard.2021.12.043 35090697
30 Chen GC, Arthur R, Mossavar-Rahmani Y, . Adherence to Recommended Eating Patterns Is Associated With Lower Risk of Peripheral Arterial Disease: Results From the Women’s Health Initiative. Hypertension. Aug 2021;78(2):447–455. doi:10.1161/HYPERTENSIONAHA.121.17432 34176290
31 Chen YY, Chen GC, Abittan N, . Healthy dietary patterns and risk of cardiovascular disease in US Hispanics/Latinos: the Hispanic Community Health Study/Study of Latinos (HCHS/SOL). Am J Clin Nutr. Oct 6 2022;116(4):920–927. doi:10.1093/ajcn/nqac199 36041183
32 Cheng E, Um CY, Prizment A, Lazovich D, Bostick RM. Associations of evolutionary-concordance diet, Mediterranean diet and evolutionary-concordance lifestyle pattern scores with all-cause and cause-specific mortality. Br J Nutr. Dec 18 2018:1–10. doi:10.1017/S0007114518003483
33 Chiuve SE, Cook NR, Shay CM, . Lifestyle-based prediction model for the prevention of CVD: the Healthy Heart Score. J Am Heart Assoc. Nov 14 2014;3(6):e000954. doi:10.1161/JAHA.114.000954 25398889
34 Choi Y, Gallaher DD, Svendsen K, . Simple Nutrient-Based Rules vs. a Nutritionally Rich Plant-Centered Diet in Prediction of Future Coronary Heart Disease and Stroke: Prospective Observational Study in the US. Nutrients. Jan 21 2022;14(3)doi:10.3390/nu14030469
35 Choi Y, Larson N, Steffen LM, . Plant-Centered Diet and Risk of Incident Cardiovascular Disease During Young to Middle Adulthood. J Am Heart Assoc. Aug 17 2021;10(16):e020718. doi:10.1161/JAHA.120.020718 34344159
36 Chomistek AK, Chiuve SE, Eliassen AH, Mukamal KJ, Willett WC, Rimm EB. Healthy lifestyle in the primordial prevention of cardiovascular disease among young women. J Am Coll Cardiol. Jan 6 2015;65(1):43–51. doi:10.1016/j.jacc.2014.10.024 25572509
37 Cuenca-Garcia M, Artero EG, Sui X, Lee DC, Hebert JR, Blair SN. Dietary indices, cardiovascular risk factors and mortality in middle-aged adults: findings from the Aerobics Center Longitudinal Study. Ann Epidemiol. Apr 2014;24(4):297–303 e2. doi:10.1016/j.annepidem.2014.01.007 24529647
38 Dai J, Krasnow RE, Reed T. Midlife moderation-quantified healthy diet and 40-year mortality risk from CHD: the prospective National Heart, Lung, and Blood Institute Twin Study. Br J Nutr. Jul 2016;116(2):326–34. doi:10.1017/S0007114516001914 27188259
39 Del Gobbo LC, Kalantarian S, Imamura F, . Contribution of Major Lifestyle Risk Factors for Incident Heart Failure in Older Adults: The Cardiovascular Health Study. JACC Heart Fail. Jul 2015;3(7):520–528. doi:10.1016/j.jchf.2015.02.009 26160366
40 Djousse L, Ho YL, Nguyen XT, . DASH Score and Subsequent Risk of Coronary Artery Disease: The Findings From Million Veteran Program. J Am Heart Assoc. Apr 21 2018;7(9)doi:10.1161/JAHA.117.008089
41 Du S, Kim H, Rebholz CM. Higher Ultra-Processed Food Consumption Is Associated with Increased Risk of Incident Coronary Artery Disease in the Atherosclerosis Risk in Communities Study. J Nutr. Dec 3 2021;151(12):3746–3754. doi:10.1093/jn/nxab285 34494108
42 Fan H, Wang Y, Ren Z, . Mediterranean diet lowers all-cause and cardiovascular mortality for patients with metabolic syndrome. Diabetol Metab Syndr. May 23 2023;15(1):107. doi:10.1186/s13098-023-01052-7 37221569
43 Fung TT, Isanaka S, Hu FB, Willett WC. International food group-based diet quality and risk of coronary heart disease in men and women. Am J Clin Nutr. Jan 1 2018;107(1):120–129. doi:10.1093/ajcn/nqx015 29381797
44 Fung TT, Pan A, Hou T, . Food quality score and the risk of coronary artery disease: a prospective analysis in 3 cohorts. Am J Clin Nutr. Jul 2016;104(1):65–72. doi:10.3945/ajcn.116.130393 27281310
45 George SM, Ballard-Barbash R, Manson JE, . Comparing indices of diet quality with chronic disease mortality risk in postmenopausal women in the Women’s Health Initiative Observational Study: evidence to inform national dietary guidance. Am J Epidemiol. Sep 15 2014;180(6):616–25. doi:10.1093/aje/kwu173 25035143
46 George SM, Reedy J, Cespedes Feliciano EM, . Alignment of Dietary Patterns With the Dietary Guidelines for Americans 2015-2020 and Risk of All-Cause and Cause-Specific Mortality in the Women’s Health Initiative Observational Study. Am J Epidemiol. May 4 2021;190(5):886–892. doi:10.1093/aje/kwaa268 33325511
47 Glenn AJ, Lo K, Jenkins DJA, . Relationship Between a Plant-Based Dietary Portfolio and Risk of Cardiovascular Disease: Findings From the Women’s Health Initiative Prospective Cohort Study. J Am Heart Assoc. Aug 17 2021;10(16):e021515. doi:10.1161/JAHA.121.021515 34346245
48 Goyal P, Balkan L, Ringel JB, . The Dietary Approaches to Stop Hypertension (DASH) Diet Pattern and Incident Heart Failure. J Card Fail. May 2021;27(5):512–521. doi:10.1016/j.cardfail.2021.01.011 33962741
49 Gu X, Wang DD, Fung TT, . Dietary quality and risk of heart failure in men. Am J Clin Nutr. Aug 4 2022;116(2):378–385. doi:10.1093/ajcn/nqac119 35511594
50 Guasch-Ferre M, Li Y, Bhupathiraju SN, . Healthy Lifestyle Score Including Sleep Duration and Cardiovascular Disease Risk. Am J Prev Med. Jul 2022;63(1):33–42. doi:10.1016/j.amepre.2022.01.027 35361505
51 Harmon BE, Boushey CJ, Shvetsov YB, . Associations of key diet-quality indexes with mortality in the Multiethnic Cohort: the Dietary Patterns Methods Project. Am J Clin Nutr. Mar 2015;101(3):587–97. doi:10.3945/ajcn.114.090688 25733644
52 Hu EA, Steffen LM, Coresh J, Appel LJ, Rebholz CM. Adherence to the Healthy Eating Index-2015 and Other Dietary Patterns May Reduce Risk of Cardiovascular Disease, Cardiovascular Mortality, and All-Cause Mortality. J Nutr. Feb 1 2020;150(2):312–321. doi:10.1093/jn/nxz218 31529069
53 Inoue-Choi M, Ramirez Y, Fukunaga A, Matthews CE, Freedman ND. Association of Adherence to Healthy Lifestyle Recommendations With All-Cause and Cause-Specific Mortality Among Former Smokers. JAMA Netw Open. Sep 1 2022;5(9):e2232778. doi:10.1001/jamanetworkopen.2022.32778 36136331
54 Judd SE, Gutierrez OM, Newby PK, . Dietary patterns are associated with incident stroke and contribute to excess risk of stroke in black Americans. Stroke. Dec 2013;44(12):3305–11. doi:10.1161/STROKEAHA.113.002636 24159061
55 Juul F, Vaidean G, Lin Y, Deierlein AL, Parekh N. Ultra-Processed Foods and Incident Cardiovascular Disease in the Framingham Offspring Study. J Am Coll Cardiol. Mar 30 2021;77(12):1520–1531. doi:10.1016/j.jacc.2021.01.047 33766258
56 Kauffman SAE, Averill MM, Delaney JAC, Lemaitre RN, Howard BV, Fretts AM. Associations of diet quality and blood serum lipoprotein levels in a population at high risk for diabetes: the Strong Heart Family Study. Eur J Clin Nutr. Jul 2020;74(7):1084–1090. doi:10.1038/s41430-019-0539-1 31804627
57 Keaver L, Ruan M, Chen F, . Plant- and animal-based diet quality and mortality among US adults: a cohort study. Br J Nutr. Jun 28 2021;125(12):1405–1415. doi:10.1017/S0007114520003670 32943123
58 Kim H, Caulfield LE, Garcia-Larsen V, Steffen LM, Coresh J, Rebholz CM. Plant-Based Diets Are Associated With a Lower Risk of Incident Cardiovascular Disease, Cardiovascular Disease Mortality, and All-Cause Mortality in a General Population of Middle-Aged Adults. J Am Heart Assoc. Aug 20 2019;8(16):e012865. doi:10.1161/JAHA.119.012865 31387433
59 Kim H, Caulfield LE, Rebholz CM. Healthy Plant-Based Diets Are Associated with Lower Risk of All-Cause Mortality in US Adults. J Nutr. Apr 1 2018;148(4):624–631. doi:10.1093/jn/nxy019 29659968
60 Kim H, Hu EA, Rebholz CM. Ultra-processed food intake and mortality in the USA: results from the Third National Health and Nutrition Examination Survey (NHANES III, 1988-1994). Public Health Nutr. Jul 2019;22(10):1777–1785. doi:10.1017/S1368980018003890 30789115
61 Kim H, Rebholz CM, Garcia-Larsen V, Steffen LM, Coresh J, Caulfield LE. Operational Differences in Plant-Based Diet Indices Affect the Ability to Detect Associations with Incident Hypertension in Middle-Aged US Adults. J Nutr. Apr 1 2020;150(4):842–850. doi:10.1093/jn/nxz275 31722418
62 Kim Y, Lu S, Ho JE, . Proteins as Mediators of the Association Between Diet Quality and Incident Cardiovascular Disease and All-Cause Mortality: The Framingham Heart Study. J Am Heart Assoc. Sep 21 2021;10(18):e021245. doi:10.1161/JAHA.121.021245 34482708
63 Kong NW, Ning H, Zhong VW, . Association between diet quality and incident cardiovascular disease stratified by body mass index. Am J Prev Cardiol. Dec 2021;8:100298. doi:10.1016/j.ajpc.2021.100298 34888539
64 Lara KM, Levitan EB, Gutierrez OM, . Dietary Patterns and Incident Heart Failure in U.S. Adults Without Known Coronary Disease. J Am Coll Cardiol. Apr 30 2019;73(16):2036–2045. doi:10.1016/j.jacc.2019.01.067 31023426
65 Li H, Zeng X, Wang Y, . A prospective study of healthful and unhealthful plant-based diet and risk of overall and cause-specific mortality. Eur J Nutr. Feb 2022;61(1):387–398. doi:10.1007/s00394-021-02660-7 34379193
66 Li J, Lee DH, Hu J, . Dietary Inflammatory Potential and Risk of Cardiovascular Disease Among Men and Women in the U.S. J Am Coll Cardiol. Nov 10 2020;76(19):2181–2193. doi:10.1016/j.jacc.2020.09.535 33153576
67 Li Y, Pan A, Wang DD, . Impact of Healthy Lifestyle Factors on Life Expectancies in the US Population. Circulation. Jul 24 2018;138(4):345–355. doi:10.1161/CIRCULATIONAHA.117.032047 29712712
68 Liese AD, Wambogo E, Lerman JL, . Variations in Dietary Patterns Defined by the Healthy Eating Index 2015 and Associations with Mortality: Findings from the Dietary Patterns Methods Project. J Nutr. Mar 3 2022;152(3):796–804. doi:10.1093/jn/nxab383 34755860
69 Mattei J, Sotos-Prieto M, Bigornia SJ, Noel SE, Tucker KL. The Mediterranean Diet Score Is More Strongly Associated with Favorable Cardiometabolic Risk Factors over 2 Years Than Other Diet Quality Indexes in Puerto Rican Adults. J Nutr. Apr 2017;147(4):661–669. doi:10.3945/jn.116.245431 28275099
70 Mursu J, Steffen LM, Meyer KA, Duprez D, Jacobs DR, Jr. Diet quality indexes and mortality in postmenopausal women: the Iowa Women’s Health Study. Am J Clin Nutr. Aug 2013;98(2):444–53. doi:10.3945/ajcn.112.055681 23783291
71 Musicus AA, Wang DD, Janiszewski M, . Health and environmental impacts of plant-rich dietary patterns: a US prospective cohort study. Lancet Planet Health. Nov 2022;6(11):e892–e900. doi:10.1016/S2542-5196(22)00243-1 36370727
72 Nazari SSH, Mokhayeri Y, Mansournia MA, Khodakarim S, Soori H. Associations between dietary risk factors and ischemic stroke: a comparison of regression methods using data from the Multi-Ethnic Study of Atherosclerosis. Epidemiol Health. 2018;40:e2018021. doi:10.4178/epih.e2018021 29807407
73 Neuhouser ML, Pettinger M, Tinker LF, . Associations of Biomarker-Calibrated Healthy Eating Index-2010 Scores with Chronic Disease Risk and Their Dependency on Energy Intake and Body Mass Index in Postmenopausal Women. J Nutr. Jan 14 2023;152(12):2808–2817. doi:10.1093/jn/nxac199 36040344
74 Noel CA, LaMonte MJ, Roberts MB, . Healthy lifestyle and risk of incident heart failure with preserved and reduced ejection fraction among post-menopausal women: The Women’s Health Initiative study. Prev Med. Sep 2020;138:106155. doi:10.1016/j.ypmed.2020.106155 32473271
75 Ogilvie RP, Lutsey PL, Heiss G, Folsom AR, Steffen LM. Dietary intake and peripheral arterial disease incidence in middle-aged adults: the Atherosclerosis Risk in Communities (ARIC) Study. Am J Clin Nutr. Mar 2017;105(3):651–659. doi:10.3945/ajcn.116.137497 28077376
76 Pang T, Alman AC, Gray HL, Basu A, Shi L, Snell-Bergeon JK. Empirical dietary inflammatory pattern and metabolic syndrome: prospective association in participants with and without type 1 diabetes mellitus in the coronary artery calcification in type 1 diabetes (CACTI) study. Nutr Res. Oct 2021;94:1–9. doi:10.1016/j.nutres.2021.08.001 34571214
77 Panizza CE, Shvetsov YB, Harmon BE, . Testing the Predictive Validity of the Healthy Eating Index-2015 in the Multiethnic Cohort: Is the Score Associated with a Reduced Risk of All-Cause and Cause-Specific Mortality? Nutrients. Apr 5 2018;10(4)doi:10.3390/nu10040452
78 Park YM, Fung TT, Steck SE, . Diet Quality and Mortality Risk in Metabolically Obese Normal-Weight Adults. Mayo Clin Proc. Oct 2016;91(10):1372–1383. doi:10.1016/j.mayocp.2016.06.022 27712636
79 Park YM, Steck SE, Fung TT, . Mediterranean diet and mortality risk in metabolically healthy obese and metabolically unhealthy obese phenotypes. Int J Obes (Lond). Oct 2016;40(10):1541–1549. doi:10.1038/ijo.2016.114 27339604
80 Patel YR, Robbins JM, Gaziano JM, Djousse L. Mediterranean, DASH, and Alternate Healthy Eating Index Dietary Patterns and Risk of Death in the Physicians’ Health Study. Nutrients. May 31 2021;13(6)doi:10.3390/nu13061893
81 Rai SK, Gortmaker SL, Hu FB, . A South Asian Mediterranean-style diet is associated with favorable adiposity measures and lower diabetes risk: The MASALA cohort. Obesity (Silver Spring). Jun 2023;31(6):1697–1706. doi:10.1002/oby.23759 37203330
82 Rebholz CM, Kim H, Ma J, Jacques PF, Levy D, Lichtenstein AH. Diet Indices Reflecting Changes to Dietary Guidelines for Americans from 1990 to 2015 Are More Strongly Associated with Risk of Coronary Artery Disease Than the 1990 Diet Index. Curr Dev Nutr. Dec 2019;3(12):nzz123. doi:10.1093/cdn/nzz123 32154494
83 Reedy J, Krebs-Smith SM, Miller PE, . Higher diet quality is associated with decreased risk of all-cause, cardiovascular disease, and cancer mortality among older adults. J Nutr. Jun 2014;144(6):881–9. doi:10.3945/jn.113.189407 24572039
84 Reedy J, Lerman JL, Krebs-Smith SM, . Evaluation of the Healthy Eating Index-2015. J Acad Nutr Diet. Sep 2018;118(9):1622–1633. doi:10.1016/j.jand.2018.05.019 30146073
85 Santiago-Torres M, Shi Z, Tinker LF, . Diet quality indices and risk of metabolic syndrome among postmenopausal women of Mexican ethnic descent in the Women’s Health Initiative Observational Study. Nutr Healthy Aging. Nov 3 2020;5(4):261–272. doi:10.3233/NHA-190076 33367152
86 Satija A, Bhupathiraju SN, Spiegelman D, . Healthful and Unhealthful Plant-Based Diets and the Risk of Coronary Heart Disease in U.S. Adults. J Am Coll Cardiol. Jul 25 2017;70(4):411–422. doi:10.1016/j.jacc.2017.05.047 28728684
87 Schrauben SJ, Hsu JY, Amaral S, Anderson AH, Feldman HI, Dember LM. Effect of Kidney Function on Relationships between Lifestyle Behaviors and Mortality or Cardiovascular Outcomes: A Pooled Cohort Analysis. J Am Soc Nephrol. Mar 2021;32(3):663–675. doi:10.1681/ASN.2020040394 33547215
88 Shah NS, Leonard D, Finley CE, . Dietary Patterns and Long-Term Survival: A Retrospective Study of Healthy Primary Care Patients. Am J Med. Jan 2018;131(1):48–55. doi:10.1016/j.amjmed.2017.08.010 28860032
89 Shams-White MM, Brockton NT, Mitrou P, Kahle LL, Reedy J. The 2018 World Cancer Research Fund/American Institute for Cancer Research (WCRF/AICR) Score and All-Cause, Cancer, and Cardiovascular Disease Mortality Risk: A Longitudinal Analysis in the NIH-AARP Diet and Health Study. Curr Dev Nutr. Jun 2022;6(6):nzac096. doi:10.1093/cdn/nzac096 35755938
90 Shan Z, Li Y, Baden MY, . Association Between Healthy Eating Patterns and Risk of Cardiovascular Disease. JAMA Intern Med. Aug 1 2020;180(8):1090–1100. doi:10.1001/jamainternmed.2020.2176 32539102
91 Shan Z, Wang F, Li Y, . Healthy Eating Patterns and Risk of Total and Cause-Specific Mortality. JAMA Intern Med. Feb 1 2023;183(2):142–153. doi:10.1001/jamainternmed.2022.6117 36622660
92 Shikany JM, Safford MM, Newby PK, Durant RW, Brown TM, Judd SE. Southern Dietary Pattern is Associated With Hazard of Acute Coronary Heart Disease in the Reasons for Geographic and Racial Differences in Stroke (REGARDS) Study. Circulation. Sep 1 2015;132(9):804–14. doi:10.1161/CIRCULATIONAHA.114.014421 26260732
93 Shikany JM, Safford MM, Soroka O, . Mediterranean Diet Score, Dietary Patterns, and Risk of Sudden Cardiac Death in the REGARDS Study. J Am Heart Assoc. Jul 6 2021;10(13):e019158. doi:10.1161/JAHA.120.019158 34189926
94 Shvetsov YB, Harmon BE, Ettienne R, . The influence of energy standardisation on the alternate Mediterranean diet score and its association with mortality in the Multiethnic Cohort. Br J Nutr. Nov 2016;116(9):1592–1601. doi:10.1017/S0007114516003482 27766989
95 Song Y, Chang Z, Cui K, . The value of the MIND diet in the primary and secondary prevention of hypertension: A cross-sectional and longitudinal cohort study from NHANES analysis. Front Nutr. 2023;10:1129667. doi:10.3389/fnut.2023.1129667 36998902
96 Sotos-Prieto M, Bhupathiraju SN, Mattei J, . Changes in Diet Quality Scores and Risk of Cardiovascular Disease Among US Men and Women. Circulation. Dec 8 2015;132(23):2212–9. doi:10.1161/CIRCULATIONAHA.115.017158 26644246
97 Sotos-Prieto M, Bhupathiraju SN, Mattei J, . Association of Changes in Diet Quality with Total and Cause-Specific Mortality. N Engl J Med. Jul 13 2017;377(2):143–153. doi:10.1056/NEJMoa1613502 28700845
98 Steffen LM, Van Horn L, Daviglus ML, . A modified Mediterranean diet score is associated with a lower risk of incident metabolic syndrome over 25 years among young adults: the CARDIA (Coronary Artery Risk Development in Young Adults) study. Br J Nutr. Nov 28 2014;112(10):1654–61. doi:10.1017/S0007114514002633 25234439
99 Tharrey M, Mariotti F, Mashchak A, Barbillon P, Delattre M, Fraser GE. Patterns of plant and animal protein intake are strongly associated with cardiovascular mortality: the Adventist Health Study-2 cohort. Int J Epidemiol. Oct 1 2018;47(5):1603–1612. doi:10.1093/ije/dyy030 29618018
100 Troeschel AN, Hartman TJ, Flanders WD, Akinyemiju T, Judd S, Bostick RM. A novel evolutionary-concordance lifestyle score is inversely associated with all-cause, all-cancer, and all-cardiovascular disease mortality risk. Eur J Nutr. Sep 2021;60(6):3485–3497. doi:10.1007/s00394-021-02529-9 33675389
101 Tsivgoulis G, Psaltopoulou T, Wadley VG, . Adherence to a Mediterranean diet and prediction of incident stroke. Stroke. Mar 2015;46(3):780–5. doi:10.1161/STROKEAHA.114.007894 25628306
102 Wang CR, Hu TY, Hao FB, . Type 2 Diabetes-Prevention Diet and All-Cause and Cause-Specific Mortality: A Prospective Study. Am J Epidemiol. Feb 19 2022;191(3):472–486. doi:10.1093/aje/kwab265 34729579
103 Wang D, Karvonen-Gutierrez CA, Jackson EA, . Western Dietary Pattern Derived by Multiple Statistical Methods Is Prospectively Associated with Subclinical Carotid Atherosclerosis in Midlife Women. J Nutr. Mar 1 2020;150(3):579–591. doi:10.1093/jn/nxz270 31687759
104 Wang P, Song M, Eliassen AH, . Optimal dietary patterns for prevention of chronic disease. Nat Med. Mar 2023;29(3):719–728. doi:10.1038/s41591-023-02235-5 36914892
105 Wang Y, Chen B, Zhang J, . Diets with higher insulinaemic potential are associated with increased risk of overall and cardiovascular disease-specific mortality. Br J Nutr. Nov 28 2022;128(10):2011–2020. doi:10.1017/S0007114521004815 34863319
106 Wang Y, Fan H, Ren Z, Liu X, Niu X. Sleep disorder, Mediterranean diet, and all-cause and cause-specific mortality: a prospective cohort study. BMC Public Health. May 18 2023;23(1):904. doi:10.1186/s12889-023-15870-x 37202744
107 Weng LC, Steffen LM, Szklo M, Nettleton J, Chambless L, Folsom AR. A diet pattern with more dairy and nuts, but less meat is related to lower risk of developing hypertension in middle-aged adults: the Atherosclerosis Risk in Communities (ARIC) study. Nutrients. May 21 2013;5(5):1719–33. doi:10.3390/nu5051719 23698164
108 Weston LJ, Kim H, Talegawkar SA, Tucker KL, Correa A, Rebholz CM. Plant-based diets and incident cardiovascular disease and all-cause mortality in African Americans: A cohort study. PLoS Med. Jan 2022;19(1):e1003863. doi:10.1371/journal.pmed.1003863 34986145
109 Whalen KA, Judd S, McCullough ML, Flanders WD, Hartman TJ, Bostick RM. Paleolithic and Mediterranean Diet Pattern Scores Are Inversely Associated with All-Cause and Cause-Specific Mortality in Adults. J Nutr. Apr 2017;147(4):612–620. doi:10.3945/jn.116.241919 28179490
110 Xu Z, Steffen LM, Selvin E, Rebholz CM. Diet quality, change in diet quality and risk of incident CVD and diabetes. Public Health Nutr. Feb 2020;23(2):329–338. doi:10.1017/S136898001900212X 31511110
111 Yu D, Sonderman J, Buchowski MS, . Healthy Eating and Risks of Total and Cause-Specific Death among Low-Income Populations of African-Americans and Other Adults in the Southeastern United States: A Prospective Cohort Study. PLoS Med. May 2015;12(5):e1001830; discussion e1001830. doi:10.1371/journal.pmed.1001830 26011727
112 Yuan S, He J, Wu S, . Trends in dietary patterns over the last decade and their association with long-term mortality in general US populations with undiagnosed and diagnosed diabetes. Nutr Diabetes. Apr 19 2023;13(1):5. doi:10.1038/s41387-023-00232-8 37076479
113 Zhang Y, Li D, Zhang H. Associations of the Healthy Eating Index-2010 with risk of all-cause and heart disease mortality among adults with hypertension: Results from the National Health and Nutrition Examination Survey 2007-2014. Front Nutr. 2023;10:1077896. doi:10.3389/fnut.2023.1077896 36937360
114 Zhong GC, Gu HT, Peng Y, . Association of ultra-processed food consumption with cardiovascular mortality in the US population: long-term results from a large prospective multicenter study. Int J Behav Nutr Phys Act. Feb 3 2021;18(1):21. doi:10.1186/s12966-021-01081-3 33536027
115 Zhong VW, Ning H, Van Horn L, . Diet Quality and Long-Term Absolute Risks for Incident Cardiovascular Disease and Mortality. Am J Med. Apr 2021;134(4):490–498 e24. doi:10.1016/j.amjmed.2020.08.012 32941845
116 Jeong SY, Wee CC, Kovell LC, . Effects of Diet on 10-Year Atherosclerotic Cardiovascular Disease Risk (from the DASH Trial). Am J Cardiol. Jan 15 2023;187:10–17. doi:10.1016/j.amjcard.2022.10.019 36459731
117 Juraschek SP, Woodward M, Sacks FM, Carey VJ, Miller ER, 3rd, Appel LJ. Time Course of Change in Blood Pressure From Sodium Reduction and the DASH Diet. Hypertension. Nov 2017;70(5):923–929. doi:10.1161/HYPERTENSIONAHA.117.10017 28993451
118 Krishnan S, Adams SH, Allen LH, . A randomized controlled-feeding trial based on the Dietary Guidelines for Americans on cardiometabolic health indexes. Am J Clin Nutr. Aug 1 2018;108(2):266–278. doi:10.1093/ajcn/nqy113 30101333
119 Prentice RL, Aragaki AK, Howard BV, . Low-Fat Dietary Pattern among Postmenopausal Women Influences Long-Term Cancer, Cardiovascular Disease, and Diabetes Outcomes. J Nutr. Sep 1 2019;149(9):1565–1574. doi:10.1093/jn/nxz107 31175807
120 Schroeder N, Park YH, Kang MS, . A randomized trial on the effects of 2010 Dietary Guidelines for Americans and Korean diet patterns on cardiovascular risk factors in overweight and obese adults. J Acad Nutr Diet. Jul 2015;115(7):1083–92. doi:10.1016/j.jand.2015.03.023 26115560
121 Sidahmed E, Cornellier ML, Ren J, . Development of exchange lists for Mediterranean and Healthy Eating diets: implementation in an intervention trial. J Hum Nutr Diet. Oct 2014;27(5):413–25. doi:10.1111/jhn.12158 24112099
122 Tussing-Humphreys L, Lamar M, McLeod A, . Effect of Mediterranean diet and Mediterranean diet plus calorie restriction on cognition, lifestyle, and cardiometabolic health: A randomized clinical trial. Prev Med Rep. Oct 2022;29:101955. doi:10.1016/j.pmedr.2022.101955 36161108
123 Van Horn L, Aragaki AK, Howard BV, . Eating Pattern Response to a Low-Fat Diet Intervention and Cardiovascular Outcomes in Normotensive Women: The Women’s Health Initiative. Curr Dev Nutr. Mar 2020;4(3):nzaa021. doi:10.1093/cdn/nzaa021 32159070
124 Thomas SJ, Booth JN, 3rd, Dai C, . Cumulative Incidence of Hypertension by 55 Years of Age in Blacks and Whites: The CARDIA Study. J Am Heart Assoc. Jul 11 2018;7(14)doi:10.1161/JAHA.117.007988
125 Whelton SP, Silverman MG, McEvoy JW, . Predictors of Long-Term Healthy Arterial Aging: Coronary Artery Calcium Nondevelopment in the MESA Study. JACC Cardiovasc Imaging. Dec 2015;8(12):1393–1400. doi:10.1016/j.jcmg.2015.06.019 26577261
126 Li S, Zhu Y, Chavarro JE, . Healthful Dietary Patterns and the Risk of Hypertension Among Women With a History of Gestational Diabetes Mellitus: A Prospective Cohort Study. Hypertension. Jun 2016;67(6):1157–65. doi:10.1161/HYPERTENSIONAHA.115.06747 27091899
127 Buijsse B, Jacobs DR, Jr., Steffen LM, Kromhout D, Gross MD. Plasma Ascorbic Acid, A Priori Diet Quality Score, and Incident Hypertension: A Prospective Cohort Study. PLoS One. 2015;10(12):e0144920. doi:10.1371/journal.pone.0144920 26683190
128 Jiang J, Liu M, Troy LM, Bangalore S, Hayes RB, Parekh N. Concordance with DASH diet and blood pressure change: results from the Framingham Offspring Study (1991-2008). J Hypertens. Nov 2015;33(11):2223–30. doi:10.1097/HJH.0000000000000710 26259122
129 Roussell MA, Hill AM, Gaugler TL, . Effects of a DASH-like diet containing lean beef on vascular health. J Hum Hypertens. Oct 2014;28(10):600–5. doi:10.1038/jhh.2014.34 24943285