# Summary of conclusion statements and grades

The 2025 Committee answered the systematic review question, “What is the relationship between dietary patterns consumed and risk of cardiovascular disease?”, with the following conclusion statements.^*^ The grades reflects the strength of the evidence underlying the conclusion statements.

* A conclusion statement is carefully constructed, based on the evidence reviewed, to answer the systematic review question. A conclusion statement does not draw implications and should not be interpreted as dietary guidance.

### Children and Adolescents

Dietary patterns consumed by children and adolescents that are characterized by higher intakes of vegetables, fruits, legumes, nuts, whole grains, fish and/or seafood, and unsaturated fats and oils and lower intakes of red and processed meats and sugar-sweetened foods and beverages are associated with lower systolic and diastolic blood pressure and triglycerides later in life. This conclusion statement is based on evidence graded as moderate. (Grade: Moderate)

### Adults and Older adults

Dietary patterns consumed by adults and older adults that are characterized by higher intakes of vegetables, fruits, legumes, nuts, whole grains, unsaturated relative to saturated fats and lower sodium, and lower intakes of red and processed meat, refined grains, and sugar-sweetened foods and beverages are associated with lower risk of cardiovascular disease, including clinically meaningful improvements in blood lipids and blood pressure. Some of these dietary patterns also included low-fat dairy and seafood. These findings were consistent across diverse racial/ethnic groups and socioeconomic positions. This conclusion statement is based on evidence graded as strong. (Grade: Strong)

## Research recommendations

- Improve comparability across studies by standardizing diet assessment methods used across different regions and populations, as well as methods used to define dietary patterns.
- Provide repeated measures of dietary patterns using validated dietary assessment tools and methods, preferably at multiple times throughout the entire course of follow-up and provide better description of the foods and/or components consumed as part of the dietary pattern while consistently incorporating diet quality.
- Collect and report detailed information on the foods and food groups; especially, report information on legumes such that it can be categorized into beans, peas and lentils.
- Conduct well-controlled, randomized intervention studies in diverse populations, to examine the effect of dietary patterns in adults and cardiovascular diseases. Specifically, conduct trials and observational studies that exclusively or predominantly enroll certain racial/ethnic groups (i.e., American Indians, Blacks, Asians, Hispanic). Conduct studies that exclusively or predominantly enroll participants from lower socioeconomic positions.
- Control for confounding factors that impact the relationship between dietary patterns and cardiovascular disease, particularly with respect to socioeconomic position, anthropometry and physical activity.
- Report information on missingness and whether the non-participants were similar or different when compared to the participants.