# Results

## Literature search and screening results

The articles included in this systematic review were identified from two literature searches (Appendix 4). The first literature search was conducted as part of existing systematic reviews^*^ that examined dietary patterns and risk of cardiovascular disease, growth, body composition, and risk of obesity, as well as risk of type 2 diabetes outcome in a combined way. NESR analysts identified 51 articles from that literature search that examined dietary patterns and risk of cardiovascular disease that met inclusion criteria for this systematic review update and were not also included in the second literature search. The second literature search was conducted to identify articles specifically on dietary patterns and risk of cardiovascular disease since the first literature search was conducted. That second literature search yielded 13,288 search results after the removal of duplicates (Figure 2). Dual-screening resulted in the exclusion of 10,431 titles, 1,809 abstracts and 975 full-text articles. Reasons for full-text exclusion are in Appendix 5. The body of evidence includes 129 articles published since October 2019 in children and adolescents (n=19), or since January 2014 in adults and older adults (n=110). In addition, this review updated graded conclusion statements from existing reviews^*^ based on 4 articles in children and adolescents and 101 articles in adults and older adults.^†^ No articles met inclusion that examined individuals during pregnancy, or individuals during postpartum.

* Boushey C, Ard J, Bazzano L, . Dietary Patterns and Risk of Cardiovascular Disease: A Systematic Review. July 2020. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at:

† Dietary Patterns Technical Expert Collaborative and NESR Staff. A Series of Systematic Reviews on the Relationship Between Dietary Patterns and Health Outcomes. March 2014. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://nesr.usda.gov/sites/default/files/2019-06/DietaryPatternsReport-FullFinal2.pdf

The body of evidence included articles across life stages as follows:

- Children and Adolescents, N=19^1–19^
- Adults and Older adults, N=110^20–129^

Figure 2 Literature search and screen flow chart

The literature searches in PubMed, Embase, and Cochrane retrieved 13,288 records after removing duplicates. 10,431 titles, 1809 abstracts, and 975 full-texts were excluded. 51 articles were included from existing reviews, 73 articles from electronic databases and 5 articles from manual search. In total, 129 articles were included in the systematic review.

## Children and adolescents

Nineteen articles met the inclusion criteria that examined the relationship between dietary patterns consumed by children and adolescents and risk of cardiovascular diseases.^1–19^ These articles were published between January 2014 and May 2023 and included 1 randomized controlled trial (RCT)^19^ and 18 prospective cohort studies (PCS).^1–18^

### Description of the evidence

#### Population

Sample sizes ranged from N=70^19^ to N=42,112.^8^ About half of the articles did not report baseline health status of participants. One trial included 100% of the participants with metabolic syndrome.^19^ Five PCS enrolled “healthy” participants,^1,2,9,13,18^ and four articles reported that 12-27% of the participants had overweight and/or obesity at baseline.^7,11,12,16^ All studies included almost equal number of boys and girls, with the exception of Dahm et al., and Asoudeh et al., that enrolled 100% females.^8,19^

None of the articles reported specific information on race and/or ethnicity of the participants, but many indicated heritage and/or birth country of participants, e.g., 76% Dutch.^11^ Regarding the socioeconomic position (SEP) of the participants, three articles reported that the participants were from low-income setting and one additional article noted that the maternal education was ~11 years.^1,12,16,17^ Three articles had higher SEP based on reported income and/or education.^8,11,18^ Seven articles had a range of SEP based on family income and/or education,^3,5–7,10,13,15^ while five articles did not report information on SEP.^2,4,9,14,19^

Multiple articles from the same study cohort were included, but each reported unique data on dietary patterns and/or outcomes. Studies were conducted in the following countries:

○ Australia, 3 articles^5,6,10^
○ Brazil, 2 articles^12,17^
○ Germany, 1 article^15^
○ Iran, 3 articles^2,9,19^
○ Ireland, 1 article^14^
○ Mexico, 1 article^1^
○ Netherlands, 2 articles^11,18^
○ Portugal, 2 articles^7,16^
○ United Kingdom, 2 articles^3,4^
○ United States, 1 article^8^
○ Multiple countries: Germany, Belgium, Italy, Poland, and Spain, 1 article^13^

#### Intervention/Exposure and Comparator

Dietary patterns were assessed in participants ranging in age from 2 up to ~18 years. In an Iranian trial, participants were randomized to a Mediterranean diet characterized by an increased consumption of olive oil, fruit, vegetables, whole grains, and low-fat dairy products and reducing total saturated fat intake and cholesterol, sweets, meat and meat products, especially red meat. The control group was given verbal instructions to follow a usual Iranian diet. In one article, the investigators retrospectively assessed diet consumed in adolescence when the participants were ~42 years old.^8^

Dietary intake was most commonly assessed with food frequency questionnaires (FFQ) in 9 articles^1,2,5,7–9,11,16,18^ and/or food diaries in 4 articles.^3,4,10,13^ Most of the studies used a validated FFQ, however, these data were collected at a single timepoint (typically the study’s baseline).^2,7,9,11,16,18^ Food/diet diaries used multiple recalls (e.g., 2-3 recalls; some studies mention repeated measure without giving a precise number) over the period of their childhood.^3,4,10,13–15^ Two articles used 24-hr recall (multiple pass method) at ~3 years and ~6-8 years to collect dietary data.^12,17^ Methods used to examine dietary patterns included:

- Intervention^19^
- Indices/Scores in 14 articles^1–3,5,6,8–12,14,15,17,18^
- Factor/cluster analysis in 4 articles^4,7,13,16^

Study authors examined dietary patterns with a variety of labels or names. Commonly included scores were different versions of a “Mediterranean” diet or those focused on “diet quality,” and other dietary patterns were assigned a label that was unclear, such as “Lower intake”.

#### Outcome

Three articles measured CVD morbidity which included outcomes such as carotid intima thickness^10,11^ and nonfatal myocardial infarction, fatal CHD, nonfatal and fatal ischemic stroke and coronary revascularization procedures.^8^ All 19 articles measured CVD-intermediate outcomes. While many studies clinically measured lipid panel (triglycerides, LDL-C and HDL-C)^1,3–5,7,8,11,13–16,18,19^ and blood pressure (systolic and diastolic) at multiple time points, some just assessed blood pressure^6^ or lipid panel.^9,12,17^ Most articles except one^18^ reported that lipid panels were assessed using blood samples collected in a fasted state. Dahm et al., reported that hypertension and hypercholesterolemia was self-reported (although this measure was validated in earlier studies from the same cohort).^8^

Duration of the intervention was 12 weeks;^19^ in observational studies, the follow-up duration ranged between ~2 years^18^ up to ~14 years.^7^ Half of the articles assessed both exposures and outcomes during childhood.^6,10–13,15–18^ An additional 5 articles assessed dietary patterns in children, and outcomes were assessed in adolescents.^1–4,9^ Five articles assessed dietary patterns during adolescence, three of which assessed outcomes in adults.^5,7,8,14,19^

### Synthesis of the evidence

Some studies reported that alignment to a dietary pattern was associated with a lower risk of systolic blood pressure (SBP), diastolic blood pressure (DBP), and triglycerides (TG) and this is summarized in detail below and in Table 6. These dietary patterns emphasized vegetables, fruits, whole grains, fish and/or seafood, legumes, nuts, unsaturated fats and oils, with lower intake of sugar-sweetened beverages and foods and red and processed meat. A small sub-set of studies reported statistically significant associations between dietary patterns characterized by higher intake of sugar-sweetened foods and beverages, red and processed meat, and lower intake of fish and seafood and higher SBP, DBP and TG.

Most or all of the articles that assessed dietary patterns and CVD morbidity,^8,10,11^ LDL-C^3,5,9,11,12,14–16,18,19^ and HDL-C^1–3,5,7,9,11,12,14–19^ showed no statistically significant associations.

- Triglyceride levels: Of the 16 articles,^1–5,7–9,11–19^ 1 trial^19^ and 3 PCS reported that greater alignment to Mediterranean,^1,19^ Dietary Guideline Index for Children and Adolescents (DGI-CA),^5^ DASH diet score,^11^ and Child Diet Quality Score (CQDS)^11^ were associated with lower TG levels in children and adolescents. Two articles reported that greater adherence to a dietary pattern with ultra-processed foods (UPF) (categorized using Nova-4 classification)^12^ and a ‘Poor quality fats and sugar’^13^ dietary pattern were each associated with greater TG levels. Many articles (11 of 16 articles) did not report an association between dietary patterns (DASH score,^1,2,9^ Mediterranean,^3,14^ other dietary score,^15,18^ UPF assessed using Nova-3, Nova-4,^17^ patterns assessed using factor/cluster analysis^7,13,16^) and TG.
- High-density lipoprotein: Of the 15 articles,^1–5,7,9,11,12,14–19^ none of the 14 PCS showed statistically significant association between a dietary pattern and HDL-C. The only trial^19^ showed that intervention group had higher HDL-C when compared to the comparator.
- Low-density lipoprotein: Of the 12 articles,^3,5,7,9,11,12,14–19^ one trial^19^ and 2 PCS^7,17^ reported an association between dietary pattern and LDL-C levels. Specifically, participants randomized to a Mediterranean pattern noticed greater reductions in LDL-C when compared to the control group (although the intervention group had higher LDL-C, perhaps due to higher baseline levels). In the PCS, participants aligning with a ‘Healthier’ dietary pattern (characterized by higher intake of seafood, soup, vegetables/legumes, fruit, added fats) and ‘Lower intake’ dietary pattern (characterized by relatively low intake in all food groups and lower energy intake) each compared to those consuming ‘Dairy’ dietary pattern (characterized by high intake in dairy products) had lower LDL-C levels.^7^ Of note, the ‘Lower intake’ pattern was considered to be slightly different than the other patterns because of its definition of lower intake of food groups. One additional article noted that higher scores for a dietary pattern with UPF (categorized using Nova-4 classification) was associated with greater LDL-C levels.^17^
- Hyperlipidemia: Dahm et al., noted lower risk of hypercholesterolemia with greater AHEI alignment.^8^ While Krijger et al. reported that participants aligned with DASH and Child diet quality score (CQDS) had lower risk of dyslipidemia,^11^ Farhadnejad et al.,^9^ showed a null association between DASH and dyslipidemia, although the direction was consistent with the findings by Krijger et al.^11^
- Blood pressure: Of the 14 articles that reported results between dietary patterns and blood pressure outcomes, 6 articles showed a statistically significant association with SBP^7,11,13,16,18,19^ and 6 articles showed a statistically significant association with DBP.^3,6,10,11,16,18^
  ○ Systolic blood pressure: Participants randomized to Mediterranean diet had statistically significant lower SBP than the control group.^19^ In addition, PCS showed that higher DASH diet scores^11^ and Diet Quality Scores^18^ were each associated with lower SBP levels. Costa et al., reported that there were significant differences in SBP among those consuming ‘Lower intake’ (vs. ‘Dairy’ and ‘Fast foods and Sweets’) dietary patterns.^7^ Also, a ‘Core’ dietary pattern (characterized by higher intakes of fruit, vegetables, potatoes, fish, white and red meat, and olive oil) was associated with lower SBP.^13^ Two other articles noted an increased risk of SBP as follows:
    ■ Pinto et al.,^16^ reported that consumption of a PCA-1 pattern (characterized by positive components such as ice cream; sausage; meat salty snacks; fish snacks; pizza & hamburger; French fries & chips; other cookies and biscuits; cakes; chocolate and chocolate snacks; sugar; candies; butter or margarine; coffee (included in the milk); Coke; carbonated soft drinks; iced tea; nectar juices; non-carbonated soft drinks and negative components such as fish (including mollusks and seafood); vegetable soup; fruit) was associated with higher SBP.
    ■ Luque et al.,^13^ reported that consumption of the ‘Protein sources’ pattern (characterized by higher intake of vegetables, potatoes, white meat, red meat, processed fish, eggs, chips and snacks, flavored milk) and ‘Poor quality fats and sugars’ pattern (characterized by higher intakes of potatoes, soft cheese, saturated spreads, fruit juices, and teas and lower intakes of fish and olive oil) were each associated with higher SBP.
  ○ Diastolic blood pressure: Greater alignment to the Children’s relative Mediterranean-style diet score (characterized by higher intake of fruit (including nuts and seeds), vegetables (excluding potatoes), pulses, cereals and cereal products, dairy products, legumes, fish and seafood, MUFA+PUFA/SFA),^3^ DASH diet score (characterized by vegetables (not potatoes and legumes); nuts and legumes; fruit and fruit Juice; whole grains; low-fat dairy and lower intake of red and processed meat; sweetened beverages),^11^ and other diet scores (Dietary score (characterized by positive components such as vegetables; fruit; milk products or alternatives; water; negative components such as fatty foods (saturated fat such as biscuits, cakes, pastries, pies, processed meats, commercial burgers, pizza, fried foods, chips, crisps, savory snacks); Sugary foods (added sugars: confectionary, sugar-sweetened drinks, cordials, fruit drinks, vitamin waters, energy and sports drinks); Sweetened drinks), Diet quality score (characterized by positive components such as vegetables; fruit; nuts; whole grains; dairy products; fish; oils and fats; negative components: meat (high fat, processed meat); sugar-containing beverages;)^6,18^ were associated with lower DBP levels. Two other articles noted an increased risk of DBP –
    ■ Kerr et al.,^10^ reported that participants who were ‘becoming less healthy’ based on Dietary score-based trajectory had increased DBP.
    ■ Pinto et al.,^16^ reported that consumption of the PLS-1 pattern (characterized by higher intake of ice cream; cheese; sausage; ham, chorizo; bread; cakes; coffee (included in the milk); Coke; carbonated soft drinks; non-carbonated soft drinks and lower intake of whole milk; vegetable soup) was associated with greater DBP.
    All 3 articles that assessed hypertension or pre-hypertension outcomes showed that greater alignment to DASH diet score^2,11^ and AHEI score^8^ was statistically associated with lower risk. The association between CQDS and pre-hypertension was not statistically significant, although the direction of effect was consistent with other articles.^11^

### Conclusion statement and grade

The 2025 Dietary Guidelines Advisory Committee developed a conclusion statement to answer the question, “What is the relationship between dietary patterns consumed and risk of cardiovascular disease for children and adolescents?” (Table 5 and Table 6).

Table 5 Conclusion statement and grade for dietary patterns consumed by children and adolescents and risk of cardiovascular disease

Conclusion Statement | Dietary patterns consumed by children and adolescents that are characterized by higher intakes of vegetables, fruits, legumes, nuts, whole grains, fish and/or seafood, and unsaturated fats and oils and lower intakes of red and processed meats and sugar-sweetened foods and beverages are associated with lower systolic and diastolic blood pressure and triglycerides later in life. This conclusion statement is based on evidence graded as moderate. (Grade: Moderate)
Grade | Moderate
Body of Evidence | 19 articles: 18 PCS and 1 RCT
Consistency | Some concerns with consistency with studies reporting heterogeneous findings. Yet, several studies showed favorable associations for certain outcomes.
Precision | Some concerns with a few studies having wider confidence intervals.
Risk of bias | Serious concerns with risk of bias with all the studies having high or very high risk of bias, primarily due to confounding and missingness.
Directness | A few concerns with populations, exposure, comparators, and outcomes were directly related to the systematic review question in most studies.
Generalizability | Serious concerns, with only one study conducted in the U.S.

#### Assessment of Evidence

This systematic review update includes 19 articles that met inclusion criteria and examined the relationship between dietary patterns consumed by children and adolescents and risk of cardiovascular disease. This body of evidence included both large and small studies with significant as well as null findings, so publication bias may have been less likely. As outlined below, the body of evidence was assessed for the following elements used when grading the strength of evidence.

##### Consistency

Despite heterogeneity, some articles reported an inverse association between the dietary patterns assessed in children and adolescents and SBP, DBP and TG levels. These dietary patterns emphasized consumption of vegetables, fruits, whole grains, fish and/or seafood, legumes, nuts, unsaturated fats and oils and were also lower in intake of sugar-sweetened beverages and foods and red and processed meat. A small sub-set of studies noted that dietary patterns characterized by higher intake of sugar-sweetened foods and beverages, red and processed meat, and lower intake of fish and seafood was associated with higher SBP, DBP and TG. A majority of the studies reported no statistically significant association between dietary pattern and HDL-C, LDL-C. All three articles that assessed hypertension or pre-hypertension reported inverse associations with a dietary pattern. The only pattern that did not show a significant association with pre-hypertension noted a consistent directionality of effect. Similarly, 2 of the 3 articles showed an inverse association with dyslipidemia, hypercholesterolemia, with the exception of one which noted consistent directionality. None of the articles that assessed CVD morbidity reported an association, irrespective of whether it was assessed in children or adults.

##### Precision

Most of the articles had reasonable sample sizes, with eight articles including over 1000 participants, including one study with 42,112 participants. A few studies demonstrated considerable variance which was characterized by wider confidence intervals.

##### Risk of bias (Table 7 and Table 8)

All included articles had risk of bias concerns, particularly due to confounding and missing data. Although many key confounders were consistently accounted for, race and/or ethnicity, physical activity and SEP were often missed. Some studies also reported that participants were significantly different than the non-participants in one or more baseline characteristics. Some studies did not provide adequate information on missing data or did not perform the analyses to suggest that the results were not biased by missing data. One article (Bull and Northstone)^4^ was weighed less during the synthesis process because of very high risk of bias. Other risk of bias concerns related to a single measurement of diet at baseline, or use of a non-fasting sample to measure blood lipids. Studies rarely had a pre-specified analysis plan and/or sometimes conducted multiple exposure and outcome analysis, which resulted in concerns with risks of bias for selection of reported results.

##### Directness

The included articles were directly designed to address the research question, as they used data from a larger cohort that intended to examine relationships between diet and health.

##### Generalizability

Most of the studies were conducted in non-U.S. settings (i.e., Australia, Brazil, Iran, Mexico and European countries). The only U.S. study included adult participants (mean age ~42 y), who retrospectively reported dietary intake during high school. A range of SEP was represented in 7 articles: 4 articles reported that the participants were from low-income settings and 3 articles reported that participants were from higher SEP based on family income and/or education. The dietary patterns considered in the studies are likely to be reflective of diets consumed in the U.S., and the outcomes are relevant to the U.S. population.

Table 6 Evidence examining the relationship between dietary patterns consumed by children and adolescents and risk of cardiovascular disease^a,*^ * Abbreviations: DM, Diabetes (T1 a/o T2); F/U, Follow-up; HOMA-IR, Homeostatic Model Assessment for Insulin Resistance; HTN, hypertension; Hx, History; ITT, intent-to-treat; MUFA, monounsaturated fatty acid; N/A, Not applicable; NR, not reported; NS, not statistically significant; Ob, Obesity; OW, Overweight; PA, Physical activity; PP, per-protocol; PUFA, polyunsaturated fatty acid; SEP/SES, Socioeconomic position/status; SFA, saturated fatty acid; T2D, Type 2 Diabetes; TC, total cholesterol; TG, triglyceride; Tx, Treatment; WC, Waist circumference; Wt, Body weight

Article Information | Intervention/exposure and comparator | Results | Methodological considerations
Aljahdali, 2022^1^; Mexico; Early Life Exposure in Mexico to Environmental Toxicants (ELEMENT); Analytic N=574; Participant characteristics:; - Health status: NR; - Race and/or Ethnicity: 100% Mexican-heritage, birth cohort; - SEP: 100% Low-mid income; 14% >12y, 36% 12 y, 49% <12y maternal education; Selection data: Enrolled pregnant mothers from lowmiddle income prenatal clinics; Included those who attended at least one of three follow-up visits; had data ≥ 1 of 8 cardiometabolic risk factors (WC, SBP, DBP, fasting glucose, TG, HDL-C, insulin, and HOMA-IR); had dietary information | DP Age(s): 8 to 14 y (time 1); 10 to 18 y (time 2); 12 to 21 y (time 3); DP and DP Components: Alternate Med Diet Score (aMED) [Fung 2005] , Positive: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA/SFA. Negative: Red and Processed Meat. Neutral: Alcohol DASH Score [Fung 2008], Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Sodium; DP Method(s): Index/Score Analysis | Age at Outcomes: 12 to 21 y, mean 16.4y (F/U: ~ 7 y); DASH & SBP, β ± SE; - Q2, β: −0.3056±0.6906; p-trend=0.6582; - Q3, β: −0.5741±0.7030; p-trend=0.4143; - Q4, β: −0.1163±0.7730; p-trend=0.8804; Cont. β: −0.02563±0.07361; p-trend=0.7277; DASH & DBP; - Q2, β: 0.1631±0.5152; p-trend=0.7517; - Q3, β: 0.1587±0.5221; p-trend=0.7613; - Q4, β: 0.1862±0.5695; p-trend=0.7437; Cont. β: 0.01777±0.05413; p-trend=0.7427; DASH & Fasting TG; - Q2, β: −0.02871±0.03882; p-trend=0.4597; - Q3, β: −0.04299±0.03956; p-trend=0.2775; - Q4, β: −0.06989±0.04442; p-trend=0.1160; Cont., β: −0.00672±0.004210; p-trend=0.1106; DASH & Fasting HDL-C; - Q2, β: 0.3541±0.7539; p-trend=0.6387; - Q3, β: 0.9758±0.7707; p-trend=0.2058; - Q4, β: 1.0360±0.8555; p-trend=0.2262; Cont., β: 0.1149±0.08184; p-trend=0.1608; aMED & SBP, β ± SE; - Q2, β: 0.5814±0.7470; p-trend=0.4366; - Q3, β: 0.4154±0.6912; p-trend=0.5479; - Q4, β: 0.4930±0.8973; p-trend=0.5828; Cont, β: 0.08428±0.1912; p-trend=0.6594; aMED &DBP; - Q2, β: −0.05008±0.5595; p-trend=0.9287; - Q3, β: −0.2620±0.5134; p-trend=0.6099; - Q4, β: 0.2122±0.6643; p-trend= 0.7495; Cont, β: −0.01518±0.1414; p-trend= 0.9145; aMED &Fasting TG; - Q2, β: −0.01424±0.04090; p-trend=0.7277; - Q3, β: −0.08973±0.03858; p-trend=0.0203; - Q4, β: −0.1316±0.05127; p-trend=0.0104; Cont, β: −0.03302±0.01077; p-trend=0.0022; aMED &Fasting HDL-C; - Q2, β: 0.1217±0.8142; p-trend=0.8812; - Q3, β: −0.00216±0.7566; p-trend=0.8812; - Q4, β: 1.8205±0.9718; p-trend=0.0614; Cont, β: 0.2389±: 0.2097; p-trend= 0.2548 | - Did not account for: Race and/or ethnicity (100% Mexican-birth cohort); Anthropometry at baseline (not accounted for in CVD results); - Diet assessment: FFQ was not formally validated; Unclear methods used to derive single estimate from multiple time pts.; - Outcome Methods: Blood samples collected fasted; Measured BP with different equipment at visit 1 than 5 (4 cuff options (XS, 17cm to L, 50cm) at visit 1 and 5 options at visit 5, 13 to 52cm); - Methodological Considerations: Time points used in analyses are unclear; Post-exposure intervention of maternal Ca+ supplementation trial in subset; 100% of participants were of Mexican-heritage, but results may not be generalizable to those not in Mexico City;; - Funding: U.S. Environmental Protection Agency; National Institute for Environmental Health Sciences; National Institute of Public Health/Ministry of Health of Mexico
Asghari, 2016^2^; Iran; Tehran Lipid and Glucose Study; Analytic N=424; Participant characteristics:; - Health status: Healthy; - Race and/or Ethnicity: NR (Iranian); - SEP: NR; Selection data: Excluded those with incomplete or missing diet or outcome data; with MetS, HTN, High TG/BP/FPG, Low HDL, or Abdominal Ob at baseline | DP Age(s):6 to 18y, mean 13.6y, at baseline; DP and DP Components: DASH score [Fung, 2008]; DASH, Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Q4 v. Q1 ref had higher vegetables (2.1x), fruits (2.4x), nuts, legumes, and seeds (1.5x), whole grains (1.5x), low fat dairy (0.6x), lower red and processed meat (0.5x), sweetened beverages (1.6x), and sodium (0.3x); DP Method(s): Index/Score Analysis | Age at Outcomes:~17y (F/U 3.6y); Hypertension; - Q2, OR: 1.18, 95% CI: 0.54, 2.58; - Q3, OR: 1.06, 95% CI: 0.48, 2.36; - Q4, OR: 0.30, 95% CI: 0.10, 0.88 P-trend: 0.045; High TG; - Q2, OR: 0.85, 95% CI: 0.33, 2.16; - Q3, OR: 0.82, 95% CI: 0.32, 2.13; - Q4, OR: 0.43, 95% CI: 0.14, 1.33 P-trend: 0.18; Low HDL-C; - Q2, OR: 1.16, 95% CI: 0.38, 3.52; - Q3, OR: 0.87, 95% CI: 0.27, 2.81; - Q4, OR: 0.82, 95% CI: 0.24, 2.80 P-trend: 0.66 | - Did not account for: Race and/or ethnicity (Iranian), Socioeconomic Position; - Diet assessment: FFQ once, validated 168-item, at baseline only; Sodium, one of the components of DASH was not precisely measured; - Outcome Methods: Blood samples collected fasted (812h); Measured BP with size-appropriate cuff (mean of 2 reads); Outcome cutpoints via NHLBI by age:; - Methodological considerations: Findings may not be entirely generalizable to U.S. population; - Funding: National Research Council of the Islamic Republic of Iran and the Research Institute for Endocrine Sciences, Shahid Beheshti University of Medical Sciences
Asodeh, 2023^19^; Iran, RCT; Analytic N=70; Selection data: Enrolled only female adolescents with metabolic syndrome who were not on a specific diet in the past 3 mo | Dietary patterns at age(s):14 y, mean; 13 to 18 y; Mediterranean diet (IG): Consumed similar vegetables, fruits, grains, meat and meat products, sugar, but significantly higher total fat, MUFA, and fiber than Control group (CG), which was assigned to usual dietary recommendations (consumed significantly less total fat, MUFA, and fiber than Mediterranean group); Method: RCT | Age at Outcome: 14 y (F/U: 12 wks); Mediterranean Diet vs. Control group, mean change ± SE:; SBP, mmHg : −7 ± 0.9 vs. −0.09 ± 0.9; p<0.001; DBP, mmHg: −0.1 ± 0.9 ± vs. −0.4 ± 0.9; p=0.85; TG, mg/dL: −25 ± 3.9 vs. −4.1 ± 3.9; p<0.01; LDL-C, mg/dL: −12.1 ± 1.9 vs. −6.1 ± 1.9; p=0.03; HDL-C, mg/dL: 3.8 ± 0.7 vs. −0.7 ± 0.7; p<0.001; Mediterranean Diet vs. Control group, mean ± SE:; SBP, mmHg : 112 ± 1.2 vs. 117 ± 1.2; p<0.001; DBP, mmHg: 73 ± 1.1 vs. 71 ± 1.1; p=0.64; TG, mg/dL: 101.7 ± 5.9 vs. 101.5 ± 5.9; p<0.001; HDL-C, mg/dL: 48.4 ± 1.1 vs. 42.3 ± 1.1; p<0.001; LDL-C, mg/dL: 87.2 ± 2.5 vs. 85.7 ± 2.5; p<0.001 | - Intensity was relatively high: control group was only given verbal instruction; - Diet adherence via 3-d diet records; - Fasted (10-12h) blood samples collected; - Funding: Tehran Endocrine and Metabolism Research Center and the Tehran University of Medical Science
Buckland, 2022^3^; United Kingdom; Avon Longitudinal Study of Parents and Children (ALSPAC); Analytic N=1940 17 y; 1961 24 y; Participant characteristics:; - Health status: BMI, mean at age 7y: ~ 16; - Race and/or Ethnicity: NR (UK birth-cohort); - SEP:26 to 43% highest HH social class; - Selection data: Excluded those diagnosed with DM, on insulin tx, or fasting glucose ≥ 7 mmol/L; those with extreme outliers on CMR score components; incomplete dietary data | DP Age(s):7y at baseline; DP and DP Components: Children’s relative Mediterranean-style diet score (C-rMED) [Buckland, 2022]; Cr-Med, Positive: Fruit (including nuts and seeds), vegetables (excluding potatoes), pulses, cereals and cereal products, dairy products, legumes, fish and seafood, MUFA+PUFA/SFA. Negative: meat and meat products; DP Method(s): Index/Score Analysis | Age at Outcomes: 17 y, 24y (F/U: ~ 11 y); c-r-Med at 7y & outcomes at age 17 y; Total cholesterol: OR: 0.92, 95% CI: 0.83, 1.01; HDL-C: OR: 0.98, 95% CI: 0.88, 1.08; LDL-C: OR: 0.98, 95% CI: 0.89, 1.08; TG: OR: 1.05, 95% CI: 0.95, 1.15; SBP: OR: 1.03, 95% CI: 0.92, 1.14; DBP: OR: 0.89, 95% CI: 0.80, 0.98; mean arterial BP: OR: 0.93, 95% CI: 0.84, 1.03; c-r-Med at 10y & outcomes at age 17 y; Total cholesterol: OR: 1.04, 95% CI: 0.94, 1.14; HDL-C: OR: 0.96, 95% CI: 0.86, 1.06; LDL-C: OR: 1.01, 95% CI: 0.92, 1.12; TG: OR: 1.05, 95% CI: 0.95, 1.15; SBP: OR: 1.07, 95% CI: 0.96, 1.19; DBP: OR: 0.99, 95% CI: 0.90, 1.10; mean arterial BP: OR: 0.95, 95% CI: 0.86, 1.05; c-r-Med at 13y & outcomes at age 17 y; Total cholesterol: OR: 0.95, 95% CI: 0.86, 1.05; HDL-C: OR: 0.97, 95% CI: 0.87, 1.07; LDL-C: OR: 1.00, 95% CI: 0.91, 1.11; TG: OR: 0.99, 95% CI: 0.90, 1.09; SBP: OR: 1.02, 95% CI: 0.91, 1.13; DBP: OR: 0.99, 95% CI: 0.89, 1.09; mean arterial BP: OR: 0.98, 95% CI: 0.88, 1.08; c-r-Med at 7y & outcomes at age 24 y; Total cholesterol: OR: 1.07, 95% CI: 0.97, 1.18; HDL-C: OR: 0.93, 95% CI: 0.84, 1.03; LDL-C: OR: 1.06, 95% CI: 0.96, 1.17; TG: OR: 0.99, 95% CI: 0.90, 1.09; SBP: OR: 0.93, 95% CI: 0.84, 1.03; DBP: OR: 0.97, 95% CI: 0.88, 1.07; mean arterial BP: OR: 0.98, 95% CI: 0.88, 1.08; c-r-Med at 10y & outcomes at age 24 y; Total cholesterol: OR: 1.04, 95% CI: 0.94, 1.14; HDL-C: OR: 0.98, 95% CI: 0.90, 1.08; LDL-C: OR: 0.99, 95% CI: 0.90, 1.09; TG: OR: 0.98, 95% CI: 0.89, 1.08; SBP: OR: 0.98, 95% CI: 0.88, 1.09; DBP: OR: 1.03, 95% CI: 0.93, 1.13; mean arterial BP: OR: 1.02, 95% CI: 0.92, 1.12; c-r-Med at 13y & outcomes at age 24 y; Total cholesterol: OR: 1.02, 95% CI: 0.92, 1.12; HDL-C: OR: 0.94, 95% CI: 0.85, 1.03; LDL-C: OR: 0.97, 95% CI: 0.88, 1.06; TG: OR: 0.99, 95% CI: 0.90, 1.09; SBP: OR: 0.95, 95% CI: 0.86, 1.04; DBP: OR: 0.94, 95% CI: 0.85, 1.05; mean arterial BP: OR: 0.94, 95% CI: 0.85, 1.04 | - Did not account for: Race and/or ethnicity, Anthropometry at baseline; - Diet assessment: 3-d diet diary at 7y (parent), 10 and 13y (parent+child help); DP based on only age 7y data; - Outcome Methods: Fasting measure of plasma lipids; - Methodological considerations: Did not adjust for repeated measurement; Missingness was an issue and children with low SES that had lower DP scores were likely to be under-represented because of attrition; - Funding: UK Medical Research Council and Wellcome, University of Bristol, Wellcome Trust and MRC, The British Heart Foundation, British Heart Foundation Research Fellowship, MRC Career Development Award
Bull and Northstone, 2016 ^4^; United Kingdom; Avon Longitudinal Study of Parents and Children (ALSPAC); Analytic N=2191; Participant characteristics:; - Health status: NR; - Race and/or Ethnicity: NR (UK birth-cohort); - SEP: NR; - Selection data: Excluded those with missing data on CV measures, dietary patterns info at all time points, and covariable data | DP Age(s): 7, 10, and 13y; “Healthy”, ref: Non-white bread, reduced-fat milk, cheese, yoghurt and fromage frais, butter, breakfast cereal, rice, pasta, eggs, fish, vegetable and vegetarian dishes, soup, salad, legumes, fruit, crackers and crispbreads, high-energy-density sauces (e.g. mayonnaise), fruit juice, water; “Processed”: Processed meat, pies and pasties, coated and fried chicken and white fish, pizza, chips, baked beans and tinned pasta, chocolate, sweets, sugar, diet and regular fizzy drinks; “Traditional”: Red meat, poultry, potatoes, vegetables, starch-based products, low-energy-density sauces, puddings, tea, coffee; “Packed Lunch”: White bread, margarine, ham and bacon, sweet spreads, salty flavourings, crisps, biscuits, diet squash, tea, coffee; Method: Factor/cluster analysis | Age at Outcomes: 17 y (F/U: ~4 y); DP at 7 y vs. SBP (>90th percentile), OR, 95% CI; Healthy: REF; Processed: 0.80, 95% CI:0.52, 1.24; P-value: 0.32; Traditional: 0.91, 95% CI: 0.60, 1.38; P-value: 0.66; Packed lunch: 1.32, 95% CI: 0.86, 2.02; P-value: 0.21; DP at 10 y vs. SBP (>90th percentile), OR, 95% CI; Healthy: REF; Processed: 1.17, 95% CI: 0·77, 1·78; P-value: 0.47; Traditional: 1.44, 95% CI: 0·96, 2·15; P-value: 0.08; Packed lunch: 0.89, 95% CI: 0·56, 1·42; P-value: 0.63; DP at 13 y vs. SBP (>90th percentile), OR, 95% CI; Healthy: REF; Processed: 0.98, 95% CI: 0.65, 1.46; P-value: 0.91; Traditional: 0.87, 95% CI: 0.57, 1.33; P-value: 0.52; Packed Lunch: 1.17, 95% CI: 0.75, 1.83; P-value: 0.49; DP at 7 y vs. DBP (>90th percentile), OR, 95% CI; Healthy: REF; Processed: 1.15, 95% CI: 0.75, 1.77; P-value: 0.52; Traditional: 1.25, 95% CI: 0.82, 1.91; P-value: 0.29; Packed Lunch: 1.44, 95% CI: 0.92, 2.26; P-value: 0.11; DP at 10 y vs. DBP (>90th percentile), OR, 95% CI; Healthy: REF; Processed: 0.87, 95% CI: 0.59, 1.29; P-value: 0.48; Traditional: 0.64, 95% CI: 0.42, 0.99; P-value: 0.05; Packed Lunch: 0.70, 95% CI: 0.44, 1.09; P-value: 0.12; DP at 13 y vs. DBP (>90th percentile), OR, 95% CI; Healthy: REF; Processed: 1.19, 95% CI: 0.81, 1.74; P-value: 0.38; Traditional: 0.80, 95% CI: 0.50, 1.26; P-vaue: 0.33; Packed Lunch: 1.53, 95% CI: 0.98, 2.40; P-value: 0.06; DP at 7 y vs. LDL-C (>90th percentile), OR, 95% CI; Healthy: REF; Processed: 0.54, 95% CI: 0.32, 0.90; P-value: 0.02; Traditional: 0.83, 95% CI: 0.53, 1.32; P-value: 0.44; Packed Lunch: 0.64, 95% CI: 0.37, 1.09; P-value: 0.10; DP at 10 y vs. LDL-C (>90th percentile), OR, 95% CI; Healthy: REF; Processed: 0.53, 95% CI: 0.32, 0.87; P-value: 0.01; Traditional: 0.62, 95% CI: 0.38, 1.01; P-value: 0.06; Packed Lunch: 0.63, 95% CI: 0.37, 1.05; P-value: 0.08; DP at 13 y vs. LDL-C (>90th percentile), OR, 95% CI; Healthy: REF; Processed: 0.67, 95% CI: 0.41, 1.07; P-value: 0.10; Traditional: 0.93, 95% CI: 0.57, 1.50; P-value: 0.75; Packed Lunch: 1.05, 95% CI: 0.62, 1.80; P-value: 0.85; DP at 7 y vs. HDL-C (>90th percentile), OR, 95% CI; Healthy: REF; Processed: 1.25, 95% CI: 0.74, 2.10; P-value: 0.40; Traditional: 1.41, 95% CI: 0.86, 2.32; P-value: 0.17; Packed Lunch: 1.83, 95% CI: 1.09, 3.05; P-value: 0.02; DP at 10 y vs. HDL-C (>90th percentile), OR, 95% CI; Healthy: REF; Processed: 0.92, 95% CI: 0.57, 1.49; P-value: 0.52; Traditional: 0.67, 95% CI: 0.40, 1.11; P-value: 0.12; Packed Lunch: 0.93, 95% CI: 0.56, 1.54; P-value: 0.77; DP at 13 y vs. HDL-C (>90th percentile), OR, 95% CI; Healthy: REF; Processed: 1.17, 95% CI: 0.73, 1.86; P-value: 0.52; Traditional: 1.32, 95% CI: 0.82, 2.14; P-value: 0.25; Packed Lunch: 1.02, 95% CI: 0.58, 1.78; P-value: 0.96; DP at 7 y vs. TG (>90th percentile), OR, 95% CI; Healthy: REF; Processed: 0.53, 95% CI: 0.32, 0.89; P-value: 0.02; Traditional: 0.82, 95% CI: 0.52, 1.30; P-value: 0.41; Packed Lunch: 0.60, 95% CI: 0.35, 1.04; P-value: 0.07; DP at 10 y vs. TG (>90th percentile), OR, 95% CI; Healthy: REF; Processed: 0.52, 95% CI: 0.32, 0.87; P-value: 0.01; Traditional: 0.58, 95% CI: 0.35, 0.95; P-value: 0.03; Packed Lunch: 0.66, 95% CI: 0.40, 1.11; P-value: 0.12; DP at 13 y vs. TG (>90th percentile), OR, 95% CI; Healthy: REF; Processed: 0.70, 95% CI: 0.44, 1.13; P-value: 0.15; Traditional: 0.91, 95% CI: 0.56, 1.48; P-value: 0.70; Packed Lunch: 1.08, 95% CI: 0.63, 1.86; P-value: 0.77 | - Did not account for: Race and/or ethnicity; Physical activity; - Diet assessment: Diet diary; Multiple dietary recall; 3-d diet diary at 7y (parent), 10 and 13y (parent+child help); 24 hr recall was used when there was no food diary; - Outcome Methods: Fasting measure of lipid profile. Friedewald equation was used to calculate LDL-C; - Methodological considerations: Participants that had missing information were more likely to adhere to processed DP and packed lunch DP.; - Funding: The United Kingdom Medical Research Council; Wellcome Trust; University of Bristol
Chan She Ping-Delfos, 2015^5^; Australia; Western Australian Pregnancy Cohort; Analytic N=1701; Participant characteristics:; - Health status: NR; - Race and/or Ethnicity: NR (Australian birth cohort); - SEP: Representative of Western Australian population; - Selection data: Excluded those with missing data, implausible energy intake | DP Age(s): 14 y; DP and DP Components: Dietary Guideline Index for Children and Adolescents (DGI-CA); DGI-CA components: Fruit/100% fruit juice, vegetables and legumes, breads and cereals, wholegrain bread relative to total, meat and alternatives (excluding processed meat); dairy products: reduced- or low-fat dairy, water as a beverage, healthy fats: total fats, <3/d ‘extra foods’; DP Method(s): Index/Score Analysis | Age at Outcomes: 17 y (F/U: ~3 y); Change in DGI-CA vs. HDL-cholesterol; β: 0.0005, 95% CI: −0.001, 0.002; P-value: 0.51; Change in DGI-CA vs. LDL-; β: −0.003, 95% CI: −0.006, 0.0002; P-value: 0.068; Change in DGI-CA vs. TAG; β: −0.003, 95% CI: −0.005, −0.0006; P-value: 0.011; Change in DGI-CA vs. SBP; β: 0.037, 95% CI: −0.008, 0.083; P-value: 0.111; Change in DGI-CA vs. DBP; β: −0.028, 95% CI: −0.06, 0.004; P-value: 0.085 | - Did not account for: Race and/or ethnicity (100% Australian-birth cohort); Anthropometry at baseline; - Diet assessment: FFQ was used to assess diet at 14 and 17 y; - Outcome Methods: Fasting blood sample of TG, HDL, LDL-C; Multiple measurement of SBP, DBP; - Methodological Considerations: Participants had lower BMI, had smaller waist circumference than non-participants, but did not differ in SES; - Funding: University of Western Australia; the Faculty of Medicine, Dentistry and Health Sciences at the University of Western Australia; the Telethon Kids Institute; the Women and Infants Research Foundation; Curtin University; and the Raine Medical Research Foundation; National Health and Medical Research Council; Telstra Research Fund; National Health and Medical Research Council
Cosier, 2023 ^6^; Australia; Early Life Longitudinal Study of Australian Children (LSAC); Analytic N=4360; Participant characteristics:; - Health status: Child birthweight z-score, mean (SD): −0.03 (1.05)~ 0.08 (1.05); - Race and/or Ethnicity:; - Australia, New Zealand and South Pacific Islands: ~84%; - Europe, USA and Canada: 8.2%; - Asia, Middle East and Africa:13.1%; - Child indigeneous status: ~1-4%; - SEP: ~23% SEIFA (Socio-Economic Indexes for Areas) relative disadvantage at follow-up, most disadvantaged; - Selection data: Excluded children whose parent 1 was not the biological mother or parent 2 was not the biological father; participants with dietary intake data not available at two or more time points, or data on BP were missing at age 10/11 yrs, data on relevant covariates were missing | DP Age(s): 4/5 y; DP and DP Components: Dietary Score [Gasser, 2019], Positive: Vegetables; Fruit; Milk products or alternatives; Water; Negative: Fatty foods (saturated fat such as biscuits, cakes, pastries, pies, processed meats, commercial burgers, pizza, fried foods, chips, crisps, savoury snacks); Sugary foods (added sugars: confectionary, sugar-sweetened drinks, cordials, fruit drinks, vitamin waters, energy and sports drinks); Sweetened drinks; DP Method(s): Index/Score Analysis | Age at Outcomes: 10/11 y (~5 y); Dietary score vs. SBP, Model adjusting BMI; Never Healthy: REF; Moderately Healthy: β: −0.83, 95% CI: −2.34, 0.67; Becoming less healthy: β: −1.28, 95% CI: −2.85, 0.29; Always healthy: β: −1.37, 95% CI: −2.82, 0.07; Model further adjusting child fat mass index; Never healthy: REF; Moderately Healthy: β: −0.70, 95% CI: −2.22, 0.82; Becoming less healthy: β: −1.21, 95% CI: −2.80, 0.38; Always healthy: β: −1.17, 95% CI: −2.64, 0.29; Dietary score vs. DBP, Model adjusting BMI; Never Healthy: REF; Moderately Healthy: β: −0.53, 95% CI: −1.77, 0.71; Becoming less healthy: β: −1.13, 95% CI: −2.43, 0.18; Always healthy: β: −1.34, 95% CI: −2.54, −0.14; Model further adjusting child fat mass index; Never healthy: REF; Moderately Healthy: β: −0.46, 95% CI: −1.70, 0.79; Becoming less healthy: β: −1.08, 95% CI: −2.38, 0.23; Always healthy: β: −1.23, 95% CI: −2.43, −0.03; No interaction between dietary trajectoies and child sex, or cohort | - Did not account for: Race and/or ethnicity; - Diet assessment: Dietary questions, scoring system and dietary trajectories not fomally validated, but data used in other studies.; - Outcome Methods: Duplicate measurement of BP. BP device not validated for use in children.; - Methodological Considerations: 57% of children were lost-to-followup. The non-participants were different in age, SBP, DBP, more likely to be poorer.; - Funding: National Institute for Health and Social Care Research, Southampton Biomedical Research Centre
Costa, 2023^7^; Portugal; EpiTEEN; Analytic N=862; Participant characteristics:; - Health status:; - BMI z scores, underweight: 1.0%; - Normal weight: 71.6%; - Overweight: 19.6%; - Obese: 7.8%; - Race and/or Ethnicity: NR (100% Portuguese); - SEP:; - ≤ 6 yrs: 17.9%; - 7-9 yrs: 17.6%; - 10-12 yrs: 31.3%; - > 12 yrs: 33.3%; - Selection data: Excluded those who did not provide dietary information at baseline, had outliers on food intake, or did not provide blood samples at 13 yr and 21 yr | DP Age(s): 13 y; DP and DP Components:; - Healthier: high in seafood, soup, vegetables/legumes, fruit, added fats; - Dairy products: high in dairy products; - Fast food and sweets: high in fast foods, sweets and pastries, soft drinks, coffee/tea; high total energy; - Lower intake: relatively low in all components; DP Method(s): Factor/Cluster Analysis | Age at Outcomes: 17, 21, 24 and 27 y (F/U: ~14 y); DP vs. TG, mg/dl (all participants); Lower intake: Mean 81, 95% CI: 76, 86; Healthier: Mean 76, 95% CI: 69, 84; Dairy Products: Mean 83, 95% CI: 77, 88; Fast food and sweets: Mean 79, 95% CI: 71, 86; P=0.415; DP vs. HDL-C, mg/dl; Lower intake: Mean 55, 95% CI: 54, 57; Healthier: Mean 53, 95% CI: 51, 55; Dairy Products: Mean 56, 95% CI: 54, 57; Fast food and sweets: Mean 54, 95% CI: 52, 57; P=0.113; DP vs. LDL-C, mg/dl; Lower intake: Mean 101, 95% CI: 98, 105; Healthier: Mean 98, 95% CI: 93, 103; Dairy Products: Mean 106, 95% CI: 102, 110; Fast food and sweets: Mean 102, 95% CI: 97, 107; P=0.015 (Significant difference between healthier & dairy; lower intake & dairy); DP & SBP, mm Hg; Lower intake: Mean 107, 95% CI: 106, 109; Healthier: Mean 108, 95% CI: 106, 109; Dairy Products: Mean 109, 95% CI: 108, 112; Fast food and sweets: Mean 110, 95% CI: 108, 112; P=0.027 (Significant difference between lower intake & dairy; lower intake & fast foods and sweets); DP & DBP, mmHg; Lower intake: Mean 68, 95% CI: 67, 69; Healthier: Mean 67, 95% CI: 66, 68; Dairy Products: Mean 68, 95% CI: 67, 69; Fast food and sweets: Mean 68, 95% CI: 67, 70; P=0.370; Among plausible reporters, n=598; TG, mg/dl; Lower intake: Mean 78, 95% CI: 72, 84; Healthier: Mean 74, 95% CI: 65, 82; Dairy Products: Mean 81, 95% CI: 75, 88; Fast food and sweets: Mean 76, 95% CI: 67, 86; P=0.397; HDL-C, mg/dl; Lower intake: Mean 56, 95% CI: 54, 58; Healthier: Mean 54, 95% CI: 51, 56; Dairy Products: Mean 56, 95% CI: 54, 58; Fast food and sweets: Mean 55, 95% CI: 52, 58; P=0.287; LDL-C, mg/dl; Lower intake: Mean 102, 95% CI: 97, 106; Healthier: Mean 97, 95% CI: 91, 103; Dairy Products: Mean 104, 95% CI: 100, 109; Fast food and sweets: Mean 102, 95% CI: 96, 109; P=0.147; SBP, mm Hg; Lower intake: Mean 107, 95% CI: 106, 108; Healthier: Mean 107, 95% CI: 105, 108; Dairy Products: Mean 108, 95% CI: 107, 110; Fast food and sweets: Mean 109, 95% CI: 107, 111; P=0.178; DBP, mmHg; Lower intake: Mean 67, 95% CI: 66, 68; Healthier: Mean 66, 95% CI: 64, 68; Dairy Products: Mean 68, 95% CI: 67, 69; Fast food and sweets: Mean 68, 95% CI: 66, 69; P=0.238 | - Did not account for: Race and/or ethnicity; - Diet assessment: FFQ; Single time point assessment of exposure; - Outcome Methods: Fasting measure of blood lipids; Duplicate measurement of BP.; - Methodological Considerations: Nonparticipants that were missing data had significantly different DP than the participants; - Funding: Portuguese Foundation for Science and Technology; Epidemiology Research Unit – Institute of Public Health, University of Porto
Dahm, 2016^8^; U.S.; Nurses’ Health Study; Analytic N=42112; Participant characteristics:; - Health status: No preexisting health conditions; BMI, kg/m2 (high school): 20.9; BMI, kg/m2 (~42 y): 24.6; - Race and/or Ethnicity:; - Predominantly White >90%; - African ancestry: 1%; - Hispanic ancestry: 1%; - Asian ancestry: 1%; - Other non-Caucasian ancestry: 2%; - SEP: 100% nurses; - Selection data: Excluded those who reported implausible daily energy during high school or adulthood; left ≥10 HS-FFQ items blank; lost to follow-up; reported CVD, or cancer prior to return of the HS-FFQ for CVD analysis, or reported diagnoses of hypercholesterolemia, hypertension, or type 2 DM prior to return of the HS-FFQ | DP Age(s): ~18 y; DP and DP Components: HS (High School)-AHEI (modified based on Alternative HEI (AHEI)-2010 [Chiuve 2012]) Positive: Vegetables, fruit, whole grains, nuts and legumes, polyunsaturated fatty acids, dark meat fish; Negative: sugar-sweetened beverages and juices, red/processed meats, trans fats, high sodium foods; DP Method(s): Index/Score Analysis | Age at Outcomes: ~55 y; HS-AHEI vs. CVD, HR, 95% CI; Q1: REF; Q2: 0.88, 95% CI: 0.65, 1.19; Q3: 1.07, 95% CI: 0.80, 1.43; Q4: 0.91, 95% CI: 0.67, 1.23; Q5: 0.92, 95% CI: 0.68, 1.25; P for trend=0.68; Per 10-point increment: HR 0.98, 95% CI: 0.87, 1.1; HS-AHEI vs. Hypercholesterolemia, HR, 95% CI (No preexisting disease); Q1: REF; Q2: 1.03, 95% CI: 0.97, 1.11; Q3: 0.91, 95% CI: 0.85, 0.98; Q4: 0.96, 95% CI: 0.90, 1.03; Q5: 0.84, 95% CI: 0.78, 0.90; P for trend< 0.001; Per 10-point Increment: HR 0.93, 95% CI: 0.91, 0.96; HS-AHEI vs. Hypertension, HR, 95% CI; Q1: REF; Q2: 0.96, 95% CI: 0.89, 1.04; Q3: 0.91, 95% CI: 0.84, 0.99; Q4: 0.97, 95% CI: 0.90, 1.05; Q5: 0.80, 95% CI: 0.74, 0.87; P for trend < 0.001; Per 10-point Increment: 0.93, 95% CI: 0.90, 0.96 | - Did not account for: Socioeconomic position (100% Nurses); - Diet assessment: FFQ; Retrospective measure of dietary recall. aHEI was modified based on data availability. Unclear if the modified aHEI was validated; - Outcome Methods: Self-reported but validated physician-diagnosed HTN and hypercholesterolemia and medication use; Non-fatal event confirmed using medical records; Death: NDI+Medical records and autopsy; Intermediate outcomes considered only in those without pre-existing conditions; - Methodological diet info was collected during adulthood and potential for recall bias, especially among this group of participants who are nurses; incidence of risk factor development in this population may be lower than the general population; Generalizability may be an issue, considering that most of the participants were White; - Funding: Carlsbergfondet Postdoc Travel Grant; the Danish Ministry of Science, Innovation and Higher Education International Network Programme; the Danish Council for Strategic Research project DIPI (Diet and Prevention of Ischemic Heart Disease: A Translational Approach); and National Institutes of Health
Farhadnejad, 2018^9^; Iran; Tehran Lipid and Glucose Study; Analytic N=430 (full sample 638); Participant characteristics:; - Health Status: Dyslipidemic; mean BMI, 21.5; Full sample: 35% Ob; 37% Central Ob; 31%; - Race and/or Ethnicity: NR (Iranian); - SEP: NR; - Selection data: Excluded those with extreme dietary intake (over/under outlier); missing info; on specific diets; or lost-to-follow-up. Also, participants with dyslipidemia, general obesity, and central obesity at baseline were excluded. | DP Age(s):14.1y mean; 10 to 18 y at baseline; DP and DP Components: DASH score [Fung, 2008]; DASH - Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; DP Method(s): Index/Score Analysis | Age at Outcomes: 17 y (F/U: ~3 y); DASH & Dyslipidemia, OR: 0.81, 95% CI: 0.30, 1.82; DASH & mean (SD); 3y-ΔTG, Q1: (42.0); Q2:−1.1 (50.0); Q3:−1.3 (43.3); Q4: 1.9 (52.9); Q5: 2.4 (43.9); P-trend: 0.93; 3y-ΔHDL-C, Q1: 0.1(8.4); Q2:−0.2 (9.0); Q3:−0.5 (9.6); Q4: −0.1 (9.5); Q5: 1.4 (9.3); P-trend: 0.53; 3y-ΔLDL-C, Q1: 1.7(20.3); Q2:2.5 (19.6); Q3:1.2 (19.6); Q4: 0.5(25.1); Q5: 2.2 (18.8); P-trend: 0.84 | - Did not account for: Race and/or ethnicity (Iranian), SEP, Physical Activity, or Anthropometry; - Diet assessment: FFQ, once at baseline; Sodium was not precisely measured; - Outcome Methods: Blood samples collected fasted (12-14h); Dyslipidemia defined as TC ≥200 mg/dL and/or TGs ≥130 mg/dL and/or LDL ≥130 mg/dL and/or HDL<40 mg/dL) after ~ 3y F/U; - Methodological Considerations: Diet measured at baseline; Study did not have enough power; Sodium was not captured precisely; - Funding: Shahid Beheshti University of Medical Sciences; Student Research Committee, Research & Technology Chancellor and Research Institute for Endocrine Sciences
Kerr, 2021^10^; Australia; Longitudinal Study of Australia Children; Analytic N=1861; Participant characteristics:; - Health Status: Mean BMIz: 0.3 [SD: 1]; above norms and aligned with national data; - Race and/or Ethnicity: NR (Australian birth-cohort); - SEP: Mean SEP: 0.32 SD above all families in LSAC Wave 1; - Selection data: Included children (enrollment at age 0-1y) sampled from Medicare database; Excluded those without sufficient data (≥2 diet scores + ≥1 outcome measure) | DP Age(s):2 to 11y across biennial waves; DP and DP Components:; Diet Quality Score categories: “Never Healthy”; “Becoming Less Healthy”; “Moderately Healthy”; “Always Healthy”;; DQS, Positive: Vegetables; Fruit; Milk products and alt.; Water. Negative: Sweetened drinks; Fatty foods; Sugary foods.; DP Method(s): Index/Score Analysis | Age at Outcomes:11.5 y (F/U: ~8 y); SBP, mean (SD); Always Healthy (AH): 108.3 (11.1); Moderately Healthy (MH): 108.4 (12.2); Becoming Less Healthy (LH): 108.9 (9.8); Never Healthy (NH): 109.9 (10.1); cont.: 0.4, 95% CI: −0.1, 0.9; ∆ 0.05; p=0.09; MH v. AH, β: 0.1, 95% CI:−1.3, 1.5; ∆0.01; p=0.92; LH v. AH, β: 0.6, 95% CI:−0.7, 1.9; ∆0.07; p=0.36; NH v. AH, β: 1.5, 95% CI:−0.3, 3.5 ;∆ 0.20; p=0.11; DBP, mean (SD); AH, 62.3 (8.0); MH, 62.2 (6.9); LH, 63.3 (6.7); NH, 63.3 (7.9); cont. β: 0.4, 95% CI: 0.1, 0.8; ∆0.07; p=0.02; MH v. AH, β: −0.1, 95% CI:−0.9, 0.8; ∆−0.01; p=0.89; LH v. AH, β: 1.0, 95% CI: 0.1, 1.9; ∆0.17; p= 0.02; NH v. AH, β: 1.0, 95% CI: −0.5, 2.5; ∆0.17; p= 0.18 | - Did not account for: Race and/or ethnicity, Physical Activity, Anthropometry; - Diet assessment: 24-h recalls (diaries), every 2y; DP from scores via groupbased trajectory modeling; - Outcome Methods: Blood samples collected semifasted (4h); Measured HR, BP, PWV; - Methodological Considerations: Findings may not be generalizable, as children from disadvantages families were under-represented; - Funding: National Health and Medical Research Council; The Royal Children’s Hospital Foundation, the Murdoch Children’s Research Institute, The University of Melbourne, the National Heart Foundation of Australia, Financial Markets Foundation for Children and the Victorian Deaf Education Institute
Krijger, 2021^11^; Netherlands; Amsterdam Born Children and their Development (ABCD); Analytic N=869; Participant characteristics:; - Health status:12% OW at age 5y; BMI mean 15.4; - Race and/or Ethnicity: 76% Dutch; 4% Surinamese, 1% Turkish, 3% Moroccan, 12% Other Western, 4% Other nonWestern; Those in lowest DASH quintile were likely to be of ethnic minority; - SEP: 7% low 20% middle, 73% high maternal education; Those in lowest DASH quintile were likely to have lower maternal education; - Selection data: Excluded those with missing data; congenital CVD; used drugs intervening with CVD factors | DP Age(s): 5 to 6y at baseline; DP and DP Components: DASH score [Fung, 2008]; CDQS [van der Velde, 2019]; DASH - Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; CDQS - Positive: fruits, vegetables, whole grains, fish, legumes, nuts, dairy, oils and soft liquid fats. Negative: sugar-containing beverages and processed meat; DP Method(s): Index/Score Analysis | Age at Outcomes:11 to 12y (F/U: ~ 6 y); Risk of preHTN; DASH: OR: 0.77, 95% CI: 0.64, 0.93; p = 0.006; CDQS: OR: 0.87, 95% CI: 0.72, 1.04; p = 0.115; Risk of dyslipidemia; DASH: OR: 0.79, 95% CI: 0.65, 0.95; p = 0.012; CDQS: OR: 0.79, 95% CI: 0.66, 0.95; p = 0.014; DASH; - LDL-C: Q1: 2.17 (0.04); Q2: 2.22 (0.04); Q3: 2.13 (0.05); Q4: 2.13 (0.05); Q5: 2.17 (0.05); p = 0.380 HDL-C: Q1: 1.42 (0.03); Q2: 1.49 (0.03); Q3: 1.51 (0.03); Q4: 1.45 (0.03); Q5: 1.47 (0.03); p = 0.592; - TG: Q1: 1.09 (0.06); Q2: 0.98 (0.06); Q3: 0.97 (0.06); Q4: 0.98 (0.06); Q5: 0.89 (0.07); p = 0.032; - SBP: Q1: 110.4 (0.06); Q2: 109.0 (0.06); Q3: 109.0 (0.07); Q4: 109.8 (0.07); Q5: 107.8 (0.08); p = 0.046; - DBP: Q1: 62.3 (0.04); Q2: 61.2 (0.04); Q3: 60.7 (0.05); Q4: 60.8 (0.05); Q5: 59.9 (0.05); p = <0.001; CDQS; - LDL-C: Q1: 2.15 (0.05); Q2: 2.13 (0.05); Q3: 2.16 (0.04); Q4: 2.18 (0.04); Q5: 2.24 (0.05); p = 0.08; - HDL-C: Q1: 1.46 (0.03); Q2: 1.46 (0.03); Q3: 1.46 (0.03); Q4: 1.47 (0.03); Q5: 1.49 (0.03); p = 0.323; - TG: Q1: 1.12 (0.06); Q2: 0.94 (0.06); Q3: 1.01 (0.06); Q4: 1.02 (0.06); Q5: 0.87 (0.06); p = 0.044; - SBP: Q1: 109.8 (0.07); Q2: 109.2 (0.07); Q3: 109.3 (0.07); Q4: 109.4 (0.06); Q5: 109.0 (0.07); p = 0.532; - DBP: Q1: 61.7 (0.05); Q2: 61.5 (0.05); Q3: 60.9 (0.05); Q4: 61.4 (0.05); Q5: 60.4 (0.05); p = 0.067 | - Did not account for: Race and/or ethnicity (75% Dutch); - Diet assessment: FFQ once at baseline (validated in age 4-6 y); - Outcome Methods: Blood samples collected fasted (ON, 8-12h) in 11-12y olds (3h finger prick in 5-6y olds); Measured BP lying and took mean of 2 reads; Outcome cut-points via NHLBI by age:; - HTN: SBP or DBP ≥ 90th percentile; Dyslipidemia: TC ≥ 5.2mmol/L or LDL >3.4 mmol/L; or HDL <0.9 mmol/L; or TG >1.7 mmol/L, or combination.; - Methodological Considerations: Issues with missing data; - Funding: Netherlands Organization for Health Research and Development, The Dutch Heart Foundation and Sarphati Amsterdam.
Leffa, 2021^12^; Brazil; NR; Analytic N=476, at age 3y; 387, at age 6y; Participant characteristics:; - Health status: Ob: 18% at age 3 y and 6 y; Children at age 6 y with abnormal lipids: TC 40%, 36% TG, 14% LDL-C, 8% HDL-C; - Race and/or Ethnicity: NR (Brazilian); - SEP: Low-income families (63% monthly income < 3x national minimum wage (~$804/mo)); Education: 29 % had <8 y shcool; 19 % of mothers were <20 y at child’s birth; - Selection data: Included pregnant mothers and children receiving Tx at primary care centers for low-income families that participated in an RCT on breast-feeding and diet practices; Excluded thost who refused participation, moved, or LFU, had incomplete diet/blood data | DP Age(s): 3 y; DP and DP Components: Nova Classification System [Monteiro, 2019]; Nova 4 (10 top sources) in rank order of median %TEI: Savoury and Biscuits (crackers, chips, salty snacks, cookies); Soft drinks (soda and sweetened juice); Sweets (candy, chocolate, ice cream); Powdered chocolate; Sugary-Milk drinks; Processed meat; Bread; Baby cereals; Ready-made soups/noodles; Margarine, mayonnaise, dressings; DP Method(s): Other UP | Age at Outcomes: 6 y (F/U: ~3 y); TC mmol/l,; T2, β: 0.19, 95 %CI: −0.01, 0.40; T3, β: 0.22, 95 %CI: 0.04, 0.39; p-trend=0.033; per 10%, β: 0.07, 95 %CI: 0.00, 0.14; p=0.046; LDL-C; T2, β: 0.10, 95 %CI: −0.10, 0.31; T3, β: 0.09, 95 %CI: −0.06, 0.23; p-trend=0.467; per 10%, β: 0.03, 95 %CI: −0.03, 0.09; p=0.331; HDL-C; T2, β: 0.04, 95 %CI: −0.03, 0.12; T3, β: 0.05, 95 %CI: −0.06, 0.15; p-trend=0.424; per 10%, β: 0.01, 95 %CI: −0.02, 0.05; p=0.334; TG mmol/l,; T2, β: 0.03, 95 %CI: −0.05, 0.11; T3, β: 0.11, 95 %CI: 0.01, 0.20; p-trend=0.04; per 10%, β: 0.04, 95 %CI: 0.01, 0.07; p=0.024 | - Did not account for: Race and/or ethnicity, Physical activity, Smoking; - Diet assessment: 24-h recall, twice at age 3y and 6y; - Outcome Methods: Blood samples collected; AHA cutoffs: TC ≥ 4.40 mmol/l, LDL-C ≥ 2.85 mmol/l; HDLC < 1.17 mmol/l; TG ≥ 0.85 mmol/l; - Methodological considerations: Data insufficiently defined for certain foods; Generalizability may be an issue.; - Funding: Brazilian Ministry of Health; Research Support Foundation of the State of Rio Grande do Sul; Brazilian National Council for Scientific and Technological Development; Coordination for the Improvement of Higher Education Personnel
Luque, 2021^13^; Germany, Belgium, Italy, Poland, and Spain; CHildhood Obesity Project (EU CHOP) trial; Analytic N=399; Participant characteristics:; - Health status: BMIz, mean at 2y 0.46 [1.21]; - Race and/or Ethnicity: 15% Germany, 19% Italy, 21% Poland, 38% Spain; - SEP:15% low, 50% medium, 35% high maternal education; - Selection data: Excluded those with incomplete dietary intake/anthropometry, BP; moved out from study region; illness or medication interfering with growth; lost contact; refusal to continue | DP Age(s): 2 y; DP and DP Components: “Core Foods Dietary Pattern”; “Poor Quality Fats and Sugars Dietary Pattern”; “Protein Sources Dietary Pattern”; Core Foods Pattern’: Higher intakes of fruit, vegetables, potatoes, fish, white and red meat, and olive oil; ‘Poor-Quality Fats and Sugars’: Positively associated with intakes of potatoes, soft cheese, saturated spreads, fruit juices, and teas and negatively associated with intakes of fish and olive oil; ‘Protein Sources’: Vegetables, potatoes, white meat, red meat, processed fish, eggs, chips and snacks, flavored milk; DP Method(s): Factor/Cluster Analysis | Age at Outcomes: 8 y (~F/U: ~ 6 y); TG; ‘Core’: β: −0.01, 95% CI: −0.03, 0.01; p=0.379; ‘Protein’: β: −0.02, 95% CI: −0.05, 0.01; p=0.131; ‘Fats and Sugars’: β: −0.06, 95% CI: −0.10, 0.04;; p=0.186; SBP; ‘Core’: β: 1.04, 95% CI: −4.13, 2.05; p=0.509; ‘Protein’: β: 5.81, 95% CI: 2.25, 9.38; p=0.001; ‘Fats and Sugars’: β: 0.73, 95% CI: −4.30, 2.83;; p=0.686; DBP; ‘Core’: β: −1.74, 95% CI: −4.37, 0.90; p=0.209; ‘Protein’: β: 2.18, 95% CI: −0.87, 5.23; p=0.160; ‘Fats and Sugars’: β: 0.79, 95% CI: −2.27, 3.85;; p=0.613; SEM, direct effects; ‘Fats and Sugars’ at 2 y & TG at 8y: β: 0.28, p<0.001; ‘Core’ at 2y & SBP at 8y: β: −0.11, p=0.034; ‘Fats and Sugars’ at 2 y & SBP at 8y: β: 0.26, p<0.001 | - Did not account for: Race and/or ethnicity, Physical activity; - Diet assessment: 3d food diaries, weighed; - Outcome Methods: Blood samples collected fasted; Measured BP and used mean of 2 reads; - Methodological Considerations: A subset of children with similar baseline characteristics were included for this study. Higher % of participants in the study had greater maternal education than the overall sample; - Funding: 5th-7th Framework Program, European Union’s Horizon 2020 research and innovation programe
McCourt, 2014^14^; Ireland; Young Hearts I & III; Analytic N=487; Participant characteristics:; - Health status: mean BMI, 19.9; 8% Smokers at baseline; - Race and/or Ethnicity: NR; - SEP:NR; - Selection data: NR | DP Age(s):12 to 15y; DP and DP Components: Mediterranean Diet Score (MDS) [Trichopolou 2003]; MDS: Positive: Vegetables; Legumes; Fruit, Nuts; Cereals; Fish; MUFA/SFA. Negative: Red and Processed Meat; Dairy Products. Neutral: Alcohol; DP Method(s): Index/Score Analysis | Age at Outcomes:20 to 25 y (F/U: ~ 8 y); TG (mmol/L), mean (SD); Least - Least adherent: 0.8 (0.4); Least - Most adherent: 0.8 (0.5); Most - Least adherent: 0.9 (0.5); Most - Most adherent: 0.8 (0.3); P=0.43; HDL (mmol/L), mean (SD); Least - Least adherent: 1.4 (0.3); Least - Most adherent: 1.4 (0.4); Most - Least adherent: 1.3 (0.3); Most - Most adherent: 1.3 (0.4); P=0.23; LDL-C (mmol/L), mean (SD); Least - Least adherent: 2.9 (0.8); Least - Most adherent: 2.7 (0.8); Most - Least adherent: 3.0 (0.9); Most - Most adherent: 3.1 (0.9); P=0.16; SBP (mm Hg), mean (SD); Least - Least adherent: 160.7 (18.2); Least - Most adherent: 159.3 (20.39); Most - Least adherent: 162.8 (17.1); Most - Most adherent: 162.4 (18.2); P=0.68; DBP (mm Hg), mean (SD); Least - Least adherent: 120.1 (18.4); Least - Most adherent: 119.2 (18.6); Most - Least adherent: 118.2 (16.8); Most - Most adherent: 123.1 (17.8); P=0.60; Δ MDS and Δ in HDL, SBP, DBP; HDL (mmol/L); Least - Least adherent: 0.0 (0.3); Least -Most adherent: 0.0 (0.4); Most - least adherent: 0.0 (0.3); Most - most adherent: 0.0 (0.4); P: 0.48; SBP (mmHg); Least - Least adherent: 46.7 (20.7); Least -Most adherent: 44.5 (22.1); Most - least adherent: 44.4 (17.4); Most - most adherent: 46.8 (18.4); P: 0.73; DBP (mmHg) Least - Least adherent: 49.5 (19.4); Least -Most adherent: 48.1 (18.4); Most - least adherent: 45.7 (19.0); Most - most adherent: 49.7 (16.3); P: 0.63 | - Did not account for: Race and/or ethnicity (Irish); - Diet assessment: 7d diet Hx at multiple time points; - Outcome Methods: Blood samples collected fasted; Measured BP and used mean of 2 reads; - Methodological Considerations: No information on participant selection criteria.; - Funding: YHI: Northern Ireland Chest, Heart and Stroke Association and Department of Health and Social Services; YHIII: Wellcome Trust, British Heart Foundation.
Montejano Vallejo, 2022^15^; Germany; DONALD (Dortmund Nutritional and Anthropometric Longitudinal Designed) Study; Analytic N=298 final sample; 284 sensitivity analysis; Participant characteristics:; - Health status: data NR; - Race and/or Ethnicity: German; - SEP: 30.5% higher education; Selection data: Excluded those <15y; had <2 WDR; missing data; underreported EI; multiple birth pregnancies; low birth weight; preterm pregnancy; those with a long f/up time | DP Age(s):>15y at baseline; DP and DP Components: EAT-Lancet Reference Dietary index (DI) score [Montejano Vallejo, 2022]; EATLR, Positive: Whole grains & all grains, ≤ 464 g/d and whole grain fiber; Tubers or starchy vegetables, ≤ 100 g/d; Vegetables, ≥ 200 - ≤ 600 g/d; Fruits, ≥ 100 - ≤ 300 g/d; Dairy foods, ≤ 500 g/d; Beef and lamb, ≤ 14 g/d; Pork, ≤ 14 g/d; Chicken and other poultry, ≤ 58 g/d; Eggs, ≤ 25 g/d; Fish, ≤ 100 g/d; Dry beans, lentils & peas, ≤ 100 g/d; Soy foods, ≤ 50 g/d; All nuts, ≥ 25 g/d; Palm oil, ≤ 6.8 g/d; Unsaturated oils, ≥ 20 - ≤ 80 g/d; Lard or tallow, ≤ 5 g/d; Butter, 0 g/d; All sweetners, ≤ 31 g/d; DP Method(s): Index/Score Analysis | Age at Outcomes: 18 y (F/U: ~3 y); LDL-C; Continuous: β: 1.01, 95% CI: 0.98, 1.03; p = 0.616; T1: β: 86.6, 95% CI: 78.6, 95.4; T2: β: 87.6, 95% CI: 79.6, 96.5; T3: β: 87.4, 95% CI: 79.4, 96.1; p = 0.981; HDL-C; Continuous: β: 1.00, 95% CI: 0.99, 1.02; p = 0.676; T1: β: 56.4, 95% CI: 52.5, 60.6; T2: β: 58.7, 95% CI: 54.7, 63.0; T3: β: 56.5, 95% CI: 52.7, 60.7; p = 0.394; TG; Continuous: β: 1.00, 95% CI: 0.96, 1.04; p = 0.999; T1: β: 76.5, 95% CI: 65.8, 89.0; T2: β: 74.4, 95% CI: 64.2, 86.3; T3: β: 74.9, 95% CI: 64.5, 86.8; p = 0.911; SBP; Continuous: β: 1.00, 95% CI: 0.99, 1.01; p = 0.925; T1: β: 144, 95% CI: 111, 117; T2: β: 114, 95% CI: 111, 117; T3: β: 115, 95% CI: 112, 118; p = 0.739; DBP; Continuous: β: 0.99, 95% CI: 0.98, 1.01; p = 0.873; T1: β: 73.2, 95% CI: 70.4, 75.9; T2: β: 71.9, 95% CI: 69.2, 74.7; T3: β: 73.7, 95% CI: 70.9, 76.6; p = 0.330 | - Did not account for: Race and/or ethnicity, Physical activity, Anthropometry (adjusted for birthweight),; - Diet assessment: 3d food diaries, weighted; - Outcome Methods: FBG collected; - Methodological Considerations: Not all KCs were accounted for; - Funding: German Federal Ministry of Education and Research grant, Ministry of Science and Research of North Rhine Westphalia, Germany
Pinto, 2020^16^; Portugal; Generation XXI birth cohort; Analytic N=3350; Participant characteristics:; - Health status: at age 10y: Ob: 17%; mean BMIz 0.72; at age 7y, 85% regular PA; - Race and/or Ethnicity: NR (Portuguese birth-cohort); - SEP: Education: 11y (SD: 4.3); - Selection data: Excluded twins; those without dietary data at 7 year-old; without cardiometabolic data at 10 year-old; without information on variables of interest | DP Age(s):7 y at baseline; DP and DP Components: PCA-1; PCA-2; PLS-1; PLS-2; LCA: EDF v. Healthier; LCA: Snacking vs. Healthier; PCA-1: Characterized by EDF (sugary drinks, sweets and salty snacks), negatively associated with Fish; Veg. soup; Fruits. Factor loadings, Positive: Ice cream; Sausage; Meat salty snacks; Fish snacks; Pizza, hamburger; French fries/chips, Cookies and biscuits; Cakes; Chocolate/snacks; Sugar; Candies; Butter or margarine; Coffee with milk; Coke; Soft drinks (Carbonated and non-carbonated); Ice Tea; Nectar juices.; PCA-2: Characterized by “healthier” foods; Factor loadings, Positive: Skim/Low-fat Milk; Yogurt; Cheese; Eggs; Ham (chorizo); Fish/seafood; Veg. soup; Vegetables (boiled and rawq); Fruitl Bread; Rice, potatoes, pasta; Crackers; Butter or margarine; Tea infusions; Natural fruit juice. Negative: Fish/seafood; Veg. soup; Fruit; PLS-1: Characterized by Processed meat, EDF (cakes; soft drinks), low in vegetables (veg. soup); Factor loadings, Positive: Ice cream; Cheese; Sausage; Ham (chorizo); Bread; Cakes; Coffee with milk; Coke; Soft drinks (Carbonated and noncarbonated). Negative: Whole milk; Veg. soup; PLS-2: Characterized by Fish; Lower intakes of EDF, Sugary drinks; Factor loadings, Positive: Fish/seafood; Negative: Chocolate milk; Ice cream; Sausage; Meat salty snakcs; Fish snacks; Pizza, hamburger; Breakfast cereals; Crackers; Cookies and biscuits; Chocolate/snacks; Coke; Soft drinks (Carbonated and noncarbonated); Ice Tea; Nectar juices.; EDF: Characterized by Sweets, soft drinks, salty pastry, processed meat; Snacking: Characterized by Snack foods, lower in fish, meat, eggs, rice, pasta, potatoes, vegetables (veg. soup); Healthier: Higher in vegetables (veg. soup), fish, and lower in EDF; DP Method(s): Factor/Cluster and Latent Class Analysis | Age at Outcomes:10 y (F/U: 3 y); PCA-1; SBPz, β: 0.035, 99% CI: 0.001, 0.069; DBPz, β: 0.018, 99% CI: −0.007, 0.043; TG, β: 0.033, 99% CI:−0.012, 0.078; HDL, β: −0.005, 99% CI: −0.051, 0.041; LDL, β:−0.013, 99% CI:−0.060, 0.034; PCA-2; SBPz, β: −0.018, 99% CI: −0.049, 0.014; DBPz, β: −0.014, 99% CI: −0.037, 0.009; TG, β: 0.002, 99% CI: −0.041, 0.045; HDL, β: −0.022, 99% CI: −0.066, 0.021; LDL, β: 0.019, 99% CI: −0.026, 0.063; PLS-1; SBPz, β: 0.011, 99% CI: −0.018, 0.040; DBPz, β: 0.022, 99% CI: 0.001, 0.043; TG, β: 0.031, 99% CI: −0.008, 0.069; HDL, β: −0.028, 99% CI: −0.067, 0.011; LDL, β: 0.025, 99% CI: −0.015, 0.065; PLS-2; SBPz, β: −0.019, 99% CI: 0.042, 0.004; DBPz, β: −0.002, 99% CI: −0.019, 0.014; TG, β: −0.011, 99% CI: −0.041, 0.020; HDL, β: −0.009, 99% CI: −0.040, 0.022; LDL, β: 0.022, 99% CI: −0.009, 0.054; EDF v. Healthier; SBPz, β: 0.053, 99% CI:−0.016, 0.122; DBPz, β: 0.036, 99% CI: −0.015, 0.087; TG, β: 0.043, 99% CI: −0.051, 0.138; HDL, β: 0.029, 99% CI: −0.067, 0.125; LDL, β: 0.001 , 99% CI: −0.098, 0.099; Snacking v. Healthier; SBPz, β: 0.074, 99% CI:−0.037, 0.185; DBPz, β: 0.069, 99% CI:−0.012, 0.151; TG, β: 0.017, 99% CI: −0.134, 0.168; HDL-C, β: 0.018, 99% CI:−0.135, 0.171; LDL-C, β: −0.103, 99% CI: −0.260, 0.054 | - Did not account for: Sex, Race and/or ethnicity (Portuguese), Socioeconomic Position; - Diet assessment: FFQ once (FFQ validated only in adults but verified by 3-d diary in sub-sample); - Outcome Methods: Blood samples collected fasted (8-10h); - Methodological Considerations: Not all KCs were accounted for. Authors have documented missingness, however, the magnitude of difference is not very high between those that completed vs. non-participating cohort at baseline.; - Funding: Programa Operacional de Saúde (Regional Department of Ministry of Health); Portuguese Foundation for Science and Technology (FCT) and by the Calouste Gulbenkian Foundation; EDER from the Operational Programme Factors of Competitiveness—COMPETE and through national funding from the FCT (Portuguese Ministry of Education and Science)
Rauber, 2015^17^; Brazil, NR; Analytic N=345; Participant characteristics:; - Health: NR; - Race and/or Ethnicity: Non-white: 56.1% at 3-4y, 58.2% at 7-8y; - SEP: Participants recruited from health centers that serve primarily low-income families; - Mean maternal education (years), 6.6-6.7; - Mean family income (USD), $3314.4-3391.3; - Selection data: Excluded HIV-positive mothers; non-full term infants (<37 weeks); children with congenital malformations; children admitted to the intensive care unit; Intially enrolled pregnant people recruited from health centers | DP Age(s): 3-4 y; DP and DP Components: Processed and Ultra-Processed Foods - NOVA 3, NOVA 4 [ Monteiro 2019] NOVA 3: Products with added substances such as salt, sugar or oil that substantially change their nature or use (e.g. canned vegetables, canned fish preserved in oil, cheese) NOVA 4: Ultra-processed products (e.g. bread, chips, cookies, candy, chocolate, soft drinks, breakfast cereal and processed meat); DP Method(s): Index/Score Analysis | Age at Outcomes: 7-8 y (F/U: ~4 y); Nova 3 (processed); ∆LDL-C, β: 1.508, 95% CI: −1.529, 4.544, P-value: 0.328; ∆non-HDL-C, β: 1.397, 95% CI: 1.780, −4.573, P-value: 0.387; ∆TG, β: −0.875, 95% CI: −4.962, 3.213, P-value: 0.673; ∆HDL-C, β: 0.060, 95% CI: −1.203, 1.322, P-value: 0.926; Nova 4 (ultra-processed); ∆LDL-C, β: 0.369, 95% CI: 0.005, 0.733, P-value: 0.047; ∆non-HDL-C, β: 0.319, 95% CI: −0.059, 0.697, P-value: 0.098; ∆TG, β: −0.465, 95% CI: −0.955, 0.025, P-value: 0.063; ∆HDL-C, β: 0.125, 95% CI: −0.026, 0.277, P-value: 0.105 | - Did not account for: Race and/or ethnicity, Physical activity; - Diet assessment: 24-hr recalls (Multiple-pass) at 3-4 y & 7-8 y; - Outcome Methods: Fasting lipid profile from venous blood samples at 7-8 years old; LDL was measured using Friedewald’s formula; - Methodological Considerations: Data from children who previously participated in a randomized trial of dietary counseling on breastfeeding and dietary practices during the first year of life; Potential overlap with another article in this dataset (Leffa et al.); - Funding: Brazil CNPq (National Funding for Research); Capes Foundation, Ministry of Education
Siddiqui, 2022^18^; The Netherlands; Generation R Study; Analytic N=3991; Participant characteristics:; - Health status: BMI, mean 16.8 at age 8 y; - Race and/or Ethnicity: 67.4% Dutch; - SEP:69% high HH income; 64% high maternal education; - Selection data: Enrolled participants at birth; Excluded those with missing FFQ or outcome data | DP Age(s):8 y; DP and DP Components: Diet Quality (DQ) Score [van der Velde, 2018]; DQS, Positive: Vegetables; Fruit; Nuts; Whole Grains; Dairy Products; Fish; Oils and fats; Negative: Meat; Sugar-containing beverages;; DP Method(s): Index/Score Analysis | Age at Outcomes:10 y (F/U: ~ 2 y); SBP, β: −0.04, 95% CI: −0.06, −0.01; DBP, β: −0.05, 95% CI: −0.07, −0.02; TG, β: −0.01, 95% CI: −0.04, 0.03; HDL-C, β: −0.01, 95% CI: −0.04, 0.03; LDL-C, β: 0.01, 95% CI: −0.05, 0.06 | - Did not account for: None (all); Anthropometry (Analyses adjusting for weight/height yielded similar results); - Diet assessment: FFQ once (baseline) (FFQ was validated in children); - Outcome Methods: Non-fasting blood samples (insulin, TG, and HDL-C); LDL-C calculated according to the Friedewald formula; % BF results were not adjusted for anthropometry but additional analyses with Weight & Height showed similar results; - Funding: Erasmus Medical Center (EMC), the Dutch Ministry of Health, Welfare, and Sports, and the Netherlands Organization for Health Research and Development

a Abbreviations:

BMI, Body mass index

BF, Body fat (total unless otherwise specified as trunk, gynoid, android, etc.)

BF%, Body fat percentage

DP, dietary pattern

DQ, diet quality

EDF, Energy-dense food

FFM, Fat-free mass

FFMI, Fat-free mass index

FM, Fat mass (total, unless otherwise specified as trunk, gynoid, android, etc.)

FMI, Fat mass index

F/U, Follow-up

HEI, Healthy Eating Index

NR, not reported;

NS, not statistically significant;

OR, Odds Ratio;

Q, quantile;

SS, regression coefficient

T, tertile

Table 7 Risk of bias for randomized controlled trials examining dietary patterns consumed by children and adolescence and risk of cardiovascular disease^a^

Article | Randomization | Deviations from intended interventions (effect of assignment) or (per-protocol) | Missing outcome data | Outcome measurement | Selection of the reported result | Overall
Asoudeh, 2023^19^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS

a Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2016 version)” ( Higgins JPT, Sterne JAC, Savović J, Page MJ, Hróbjartsson A, Boutron I, Reeves B, Eldridge S. A revised tool for assessing risk of bias in randomized trials In: Chandler J, McKenzie J, Boutron I, Welch V (editors). Cochrane Methods. Cochrane Database of Systematic Reviews 2016, Issue 10 (Suppl 1). 10.1002/14651858.CD201601. )

Table 8 Risk of bias for observational studies examining dietary patterns consumed by children and adolescence and risk of cardiovascular disease^a^

Author, year | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall
Aljahdali, 2022^1^ | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | HIGH | LOW | SOME CONCERNS | HIGH
Asghari, 2016^2^ | HIGH | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | HIGH
Buckland, 2022^3^ | HIGH | LOW | LOW | LOW | HIGH | LOW | HIGH | HIGH
Bull, 2016^4^ | HIGH | HIGH | LOW | LOW | HIGH | LOW | HIGH | VERY HIGH
Chan She Ping-Delfos, 2015^5^ | SOME CONCERNS | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Cosier, 2023^6^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | SOME CONCERNS | SOME CONCERNS | HIGH
Costa, 2023^7^ | HIGH | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Dahm, 2016^8^ | HIGH | HIGH | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Farhadnejad, 2018^9^ | HIGH | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Kerr, 2021^10^ | SOME CONCERNS | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Krijger, 2021^11^ | HIGH | SOME CONCERNS | LOW | LOW | HIGH | SOME CONCERNS | SOME CONCERNS | HIGH
Leffa, 2021^12^ | HIGH | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | HIGH | HIGH
Luque, 2021^13^ | HIGH | LOW | LOW | LOW | HIGH | SOME CONCERNS | SOME CONCERNS | HIGH
McCourt, 2014^14^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH
Montejano Vallejo, 2022^15^ | HIGH | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS | HIGH
Pinto, 2020^16^ | HIGH | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Rauber, 2015^17^ | HIGH | SOME CONCERNS | LOW | LOW | LOW | LOW | HIGH | HIGH
Siddiqui, 2022^18^ | LOW | SOME CONCERNS | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH

a Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias for Nutrition Observational Studies” tool (RoB-NObs) ( Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC. )

## Adults and Older Adults

The 2025 Dietary Guidelines Advisory Committee updated an existing systematic review^*^ by synthesizing an additional 110 articles that were published between January 2014 and May 2023 and met inclusion criteria by assessing how this new evidence relates to the conclusion statement from the existing systematic review. One hundred and ten articles met inclusion criteria examining the relationship between dietary patterns consumed by adults and older adults and risk of cardiovascular disease and had the following study designs: nine articles from RCT^116–123,129^ and 101 articles with PCS design.^20–115,124–128^

* Dietary Patterns Technical Expert Collaborative and NESR Staff. A Series of Systematic Reviews on the Relationship Between Dietary Patterns and Health Outcomes. March 2014. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://nesr.usda.gov/sites/default/files/2019-06/DietaryPatternsReport-FullFinal2.pdf

### Description of the evidence

#### Population

All included articles were conducted in the U.S., per inclusion criteria. The analytic sample size of study groups ranged from N=36^129^ up to N=48,835^119^ in RCT. For the observational studies, the sample size ranged from N=334^85^ to N=424,662.^83^ The follow-up duration ranged from 4 weeks^120^ to 8.5 years^119^ in RCT. Observational studies generally had a longer follow-up, ranging from 2 years^69^ up to 40 years.^38,115^

Nineteen articles (including three articles from two RCT) enrolled 100% female participants.^20,21,25,30,32,36,45–47,70,71,73,74,85,103,126^ These were primarily from Women’s Health Initiative, Nurses’ Health Study and Iowa Women’s Health Study. On the other hand, three studies (NHLBI Twin Study, Health Professionals Follow-up Study, Physicians’ Health Study) enrolled 100% male participants.^38,49,80^

Multiple articles from the same study were included, as long as they reported unique data (i.e., different dietary patterns, outcomes, sub-population). Following is the list of trials and cohort studies that contributed to multiple articles -

- Women’s Health Initiative Dietary Modification trial^119,123^
- DASH^116,117^
- ARIC Study^41,52,58,61,75,87,107,110^
- CARDIA^34,35,98,124,127^
- Cardiovascular Disease Lifetime Risk Pooling Project^63,115^
- Framingham Heart Study^55,62,82^
- Iowa Women’s Health Study^32,70^
- MASALA^26,81^
- Multi-Ethnic Study of Atherosclerosis^28,72^
- Multiethnic Cohort Study^22,51,77,94^
- NHANES^42,57,59,60,65,78,79,95,105,106,112,113^
- NHS I, HPFS^23,33,50,67,86,90,104^
- NHS I, NHS II, HPFS^24,43,44,66,86,90,104^
- NIH-AARP Diet and Health Study^53,83,84,89^
- Prostate, Lung, Colorectal, and Ovarian Cancer Screening Trial^105,114^
- REGARDS^27,48,54,64,92,93,100,101,109^
- Southern Community Cohort Study^29,111^
- Women’s Health Initiative^20,25,30,45–47,73,74,85^

##### Health status

Most of the RCT included participants that were at high risk of chronic diseases, such as exclusively enrolling participants with overweight and/obesity,^118,120,122^ or enrolling participants with a mean BMI >25 kg/m^2^.^116,117,119,121^ A few trials also included some participants with hypertension (26-~63%);^116,117,119,122^ however, two trials included normotensive participants^123,129^ Among observational studies, the mean BMI was ≥ 25 kg/m^2^ and/or more than half of the participants had overweight/obesity in 66 articles;^20,22,26,28–30,32,38–41,46–48,51,53,55–64,67,69–74,76,80–83,85,88,89,91–93,95–97,100–103,105,106,108,109,111–115,125–128^ one article included 100% of participants with obesity.^79^ In contrast, another article included 100% participants with BMI <25 kg/m^2^.^78^

Thirty-eight articles from observational studies included some participants with hypertension,^20,22,25,26,28–30,37,39,41,47,48,50,55,57,58,64,69–72,74–76,79–81,87,93,95,97,101,106,108,111–114^ with one article enrolling 100% of the participants with hypertension.^113^ In addition, some observational studies exclusively enrolled 100% participants with metabolic syndrome.^42^ Another article included 100% participants without hypertension.^107^ Also, of note, several articles were included from the REGARDS cohort which oversampled participants from geographical region that is at high risk of stroke.^27,54,92,93,100,101,109^

##### Race and/or Ethnicity

Racial and/or ethnic composition were reported in all but two trials.^118,129^ Three articles from 2 trials reported that >80% of the participants were White.^119,121,123^ Tussings-Humphreys reported that 91% of the participants were Non-Hispanic Black;^122^ whereas in other trials the percent of participants who were Black ranged between 7% to 57%. Other race and/ethnicities were minimally represented in trials, except for Jeong that reported that 51% were “other” which was not described further.^116^

Most observational studies reported race and/or ethnicity. Sixty-one of 101 articles included mostly White participants.^20,23–25,30,32,33,36–41,43–50,52,53,55,57–62,66–68,70,71,73,75,76,78–80,82,83,87–91,93,96,97,102,104,106–108,110,114,115,126,128^ Several studies exclusively or predominantly enrolled participants of a specific racial/ethnic background, including: 100% African American;^108^ 100% South Asian (two articles from a single cohort);^26,81^ 100% Hispanic (three cohort studies);^31,69,85^ 100% American Indian.^56^ Participants from the Multiethnic Cohort study included 30-40% of Asians (Native Hawaiians and Japanese Americans).^22,51,77,94^

##### Socioeconomic position (SEP)

Three articles from two trials reported that the majority of participants attended college.^117,119,123^ One trial noted that almost all participants had health insurance.^122^ SEP was not reported in other trials.^116,118,120,121,129^

Observational studies reported that participants were from a diverse range of SEP based on education, income, insurance status and/or other indicators of SEP. For example, 100% of the participants were enrolled in Medicare or Medicaid in one article^29^ and another article reported that ~40% did not have medical insurance;^111^ At least 14 articles reported that half of the participants had high school education or less.^31,32,38,54–56,59,69,70,74,75,111,113,114^ On the other hand, 23 of the 101 studies reported that majority of their participants were well-educated and consistently employed (e.g., nurses, health professionals, and physicians).^21,23,24,26,33,36,43,44,47,49,50,66,67,71,80,86,90,91,96,97,104,112,126^

#### Intervention/Exposure and Comparator

Dietary pattern consumption was assessed among adults and older adults (Table 10). The age range of participants was from 18 to 97 years, although mean age was mostly between 45 to 65 years. Only a few articles examined dietary patterns in younger adults (18-<45 years)^31,34–36,56,58,59,76,98,124,126,127^ and older adults (over 65 years).^39,122^ The majority of the PCS articles assessed dietary patterns only once (60 of 101 articles), usually at baseline and using a validated FFQ; some articles used two consecutive 24-hr recalls (6 articles). Thirty-five articles collected multiple assessments during follow-up. Dietary pattern methods are described below:

- Intervention, 9 articles from 7 trials^116–123,129^
- Index/Score, 93 articles (including 4 UPF articles)^20–53,55–63,66–71,73,74,76–91,93,96–98,100–102,104,106,108,110–115,124–128^
- Factor/cluster or latent-class analysis, 8 articles^54,64,68,75,92,93,99,103^
- Reduced rank regression, 3 articles^72,103,105^

Table 10 Dietary Pattern Components

Reference | Dietary pattern | Dietary pattern components
Index/Score Analysis
Aigner, 2018 ^22^ | Healthy Eating Index (HEI)- 2010 | Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; Fatty Acids (PUFA+MUFA/SFA). Negative: Refined Grains; Added Sugars in “Empty Calories”; Solid Fats in “Empty Calories”; Sodium
Aigner, 2018 ^22^ | Alternative HEI (AHEI)-2010 | Positive: Vegetables; Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol
Aigner, 2018 ^22^ | Alternate Mediterranean Diet Score (aMED) | Positive: Vegetables; Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA/SFA; Neutral: Red and Processed Meat; Neutral: Alcohol
Aigner, 2018 ^22^ | DASH | Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Sodium
Dai, 2016 ^38^ | Moderation-quantified healthy diet (MQHD) | Positive: Vegetables; Potatoes; Fruit; Grains; Fish and Shellfish; Poultry; Red Meat; Eggs; Dairy Products; Unsaturated Fatty Acids: SFA; Fried Foods: Non-Fried Foods; Alcohol
Dai, 2016 ^38^ | alternative MQHD (aMQHD) | Positive: Vegetables; Potatoes; Fruit; Nuts; Grains; Fish and Shellfish; Poultry; Red Meat; Eggs; Lamb or Veal; White: Red Meat; Dairy Products; Skimmed Milk; Ice Cream: Dairy Products; Unsaturated Fatty Acids: SFA; Fried Foods: Non-Fried Foods; Alcohol
Dai, 2016 ^38^ | Mediterranean Diet Score (MDS) | Positive: Vegetables; Legumes; Fruit, Nuts; Cereals; Fish; MUFA/SFA. Negative: Red and Processed Meat; Dairy Products. Neutral: Alcohol
Fan, 2023 ^42^ | aMED | Positive: Fruits, vegetables, whole grains, legumes, nuts, fish, the ratio of monounsaturated to saturated fat; Negative: red and processed meat; Moderation: alcohol
George, 2014 ^45^ | HEI-2010 | Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; Fatty Acids (PUFA+MUFA/SFA). Negative: Refined Grains; Added Sugars in “Empty Calories”; Solid Fats in “Empty Calories”; Sodium
George, 2014 ^45^ | AHEI-2010 | Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol
George, 2014 ^45^ | aMED | Positive: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA/SFA. Negative: Red and Processed Meat. Neutral: Alcohol
George, 2014 ^45^ | DASH | Positive: Vegetables (not potatoes and legumes); Nuts, seeds. legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Sodium
Harmon, 2015 ^51^ | HEI-2010 | Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; Fatty Acids. Negative: Refined Grains; Added Sugars in “Empty Calories”; Solid Fats in “Empty Calories”; Sodium
Harmon, 2015 ^51^ | AHEI-2010 | Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol
Harmon, 2015 ^51^ | aMED | Positive: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA/SFA. Negative: Red and Processed Meat. Neutral: Alcohol
Harmon, 2015 ^51^ | DASH | Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Sodium
Li, 2018 ^67^ | AHEI-2010 | Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; Fatty Acids. Negative: Refined Grains; Added Sugars in “Empty Calories”; Solid Fats in “Empty Calories”; Sodium
Liese, 2021 ^68^ | Healthy Eating Index (HEI)2015 | Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; PUFA+MUFA/SFA. Negative: Refined Grains; Added Sugars; SFA; Sodium
Mursu, 2013 ^70^ | AHEI-2010 | Positive: Vegetables; Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol
Mursu, 2013 ^70^ | A Priori Diet Quality Score (APDQS) | Positive: Green Vegetables, Other Vegetables, Tomato; Legumes, Beans, Soy Products; Fruit; Nuts, Seeds; Whole Grains; Fish; Poultry; Low-Fat Dairy; Oil; Tea, Coffee; Beer, Wine, Liquor. Negative: Fried potatoes; Red Meat, Liver, Processed Meat, Butter; Whole-Fat Dairy; Soft Drinks, Sweets; Salty Snacks; Fried Foods. Neutral: Potatoes; Fruit Juices; Chocolate, Diet Soft Drinks; Eggs; Margarine
Panizza, 2018 ^77^ | HEI-2015 | Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; PUFA+MUFA/SFA. Negative: Refined Grains; Added Sugars; SFA; Sodium
Park, 2016 ^78^ | HEI | Positive: Vegetables; Fruit; Grains. Negative: Meat; Milk; Total Fat, SFA, Cholesterol. Neutral: Sodium
Patel, 2021 ^80^ | aMED | Positive: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA/SFA. Negative: Red and Processed Meat. Neutral: Alcohol
Patel, 2021 ^80^ | DASH | Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Sodium
Patel, 2021 ^80^ | AHEI | Positive: Vegetables (not potatoes, French fries); Fruit; Nuts and Soy Protein; Cereal Fiber; White: Red Meat Ratio; PUFA:SFA; Multi-Vitamin Use. Negative: Trans-UFA. Neutral: Alcohol
Reedy, 2014 ^83^ | AHEI-2010 | Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: alcohol
Reedy, 2014 ^83^ | aMED | Positive: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA/SFA. Negative: Red and Processed Meat. Neutral: alcohol
Reedy, 2014 ^83^ | DASH | Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened beverages; Sodium
Reedy, 2014 ^83^ | HEI-2010 | Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; Fatty Acids. Negative: Refined Grains; Added Sugars in “Empty Calories”; Solid Fats in “Empty Calories”; Sodium
Reedy, 2018 ^84^ | HEI-2015 | Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; PUFA+MUFA/SFA. Negative: Refined Grains; Added Sugars; SFA; Sodium
Shams-White, 2022 ^89^ | World Cancer Research Fund/American Institute for Cancer Research Score - Diet Only | Positive: Vegetables and Fruit; Dietary Fiber. Negative: Red and Processed Meat; Sugary Drinks; Alcohol; Sodium; Energy-Dense Foods
Shan, 2023 ^91^ | HEI-2015 | Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; PUFA+MUFA/SFA. Moderation: Refined Grains; Added Sugars; SFA; Sodium
Shan, 2023 ^91^ | aMED | Positive: Vegetables, fruits, whole grains, nuts, legumes, fish, and ratio of monounsaturated fat to saturated fat; Negative: Red and processed meat, alcohol
Shan, 2023 ^91^ | Healthy Plant-based Diet Index (hPDI) | Positive (Healthy Plant foods): whole grains, fruits, vegetables, nuts, legumes, vegetable oils, and tea and coffee; Negative (Less healthy plant foods): fruit juices, refined grains, potatoes, sugar-sweetened beverages, and sweets and desserts; Negative (Animal foods): animal fat including butter or lard, dairy, eggs, fish and seafood, meat, and miscellaneous animal-based foods
Shan, 2023 ^91^ | AHEI-2010 | Positive: Vegetables, whole fruit, whole grains, nuts and legumes, long-chain n-3 fats, polyunsaturated fatty acids; Negative: red and processed meat, trans fat, sodium, sugar-sweetened beverages and fruit juice
Shvetsov, 2016 ^94^ | aMED | Positive: Vegetables (not potatoes); Legumes; Fruit and 100% fruit juices; Nuts; Whole Grains; Fish; MUFA/SFA. Negative: Red and Processed Meat. Neutral: alcohol
Song, 2023 ^95^ | Mediterranean-DASH Intervention for Neurodegenerative Delay (MIND) diet score | Positive: green leafy vegetables, other vegetables, nuts, berries, beans, whole grains, seafood, poultry, olive oil, and wine; Negative: red meats, butter, and stick margarine, cheese, pastries and sweets, and fried/fast food
Sotos-Prieto, 2017 ^97^ | aMED | Positive: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA/SFA. Negative: Red and Processed Meat. Neutral: alcohol
Sotos-Prieto, 2017 ^97^ | DASH | Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened beverages; Sodium
Sotos-Prieto, 2017 ^97^ | AHEI | Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: alcohol
Wang, 2021 ^102^ | Dietary diabetes riskreduction score | Positive: Cereal fiber (insoluble fiber), ratio of polyunsaturated to saturated fatty acids, coffee, and nuts; Negative: glycemic index, trans-fatty acids, red and processed meat, and sugar-sweetened beverages (soft drinks or fruit drinks)
Wang, 2023 ^106^ | aMED | Positive: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA/SFA. Negative: Red and Processed Meat. Neutral: Alcohol
Whalen, 2017 ^109^ | Mediterranean-based Diet Score | Positive: Vegetables; Fruit; Nuts; Fish; Lean Meat (skinless chicken and turkey); MUFA/SFA ratio. Negative: Red and Processed Meat (Nitrate processed meats and red meat consumption together); Sodium. Neutral: Grains and Starches (breads, rice, and white potatoes); Dairy Foods; Alcohol
Whalen, 2017 ^109^ | Paleolithic Diet Score | Positive: Vegetables; Fruit and Vegetable Diversity; Fruit; Nuts; Fish; Lean Meat (skinless chicken, veal, and turkey); Calcium (from non-dairy foods). Negative: Grains and Starches (breads, rice, and white potatoes); Baked goods; Red and Processed Meat (Nitrate processed meats and non-lean red meat (including pork); Dairy Foods; Alcohol; Sodium
Yu, 2015 ^111^ | HEI-2010 | Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; Fatty acids. Negative: Refined Grains; Added sugars in “empty calories”; Solid fats in “empty calories”; Sodium
Yuan, 2023 ^112^ | HEI-2015 | Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; PUFA+MUFA/SFA. Negative: Refined Grains; Added Sugars; SFA; Sodium
Zhang, 2023 ^113^ | HEI-2010 | Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; Fatty Acids. Negative: Refined Grains; Added Sugars in “Empty Calories”; Solid Fats in “Empty Calories”; Sodium
Agha, 2014 ^20^ | AHEI-2010 | Positive: Vegetables; Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol
Chen, 2021 ^30^ | aMED | Positive: Vegetables; Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA/SFA; Neutral: Red and Processed Meat; Neutral: Alcohol
Chen, 2021 ^30^ | AHEI-2020 | Positive: Vegetables (not potatoes, French fries); Fruit; Nuts and Soy Protein; Cereal Fiber; White: Red Meat Ratio; PUFA:SFA; Multi-Vitamin Use. Negative: Trans-UFA. Neutral: Alcohol
Chen, 2021 ^30^ | DASH | Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Sodium
Chen, 2021 ^30^ | HEI-2015 | Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; PUFA+MUFA/SFA. Negative: Refined Grains; Added Sugars; SFA; Sodium
Chen, 2022 ^31^ | aMED | Positive: Vegetables (not potatoes); Legumes; Fruit (excluding juices); Nuts; Whole Grains; Fish & shell fish; MUFA/SFA. Negative: Red and Processed Meat. Neutral: Alcohol
Chen, 2022 ^31^ | HEI-2015 | Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; PUFA+MUFA/SFA. Negative: Refined Grains; Added Sugars; SFA; Sodium
Chen, 2022 ^31^ | hPDI | Positive: Vegetables (excl potatoes); Fruits (excl juices); Nuts & Legumes; Whole grains; Vegetable oils; Tea/coffee; Negative: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Animal fats; Dairy; Eggs, Fish/seafood; White meat (poultry & fish/shellfish); Red and processed meat
Chiuve, 2014 ^33^ | Diet Composite Score | Fruits, vegetables, Nuts, Cereal Fiber, Red+Processed meat, and SSB
Choi, 2021 ^35^ | APDQS | Positive: Vegetables-Green; Vegetables-Yellow; Vegetables-Other; Tomatoes; Beans/Legumes; Fruit; Avocado; Nuts, Seeds; Soy Products; Whole Grains; Fish, fatty not fried; Fish, lean not fried; Poultry; Low-Fat Dairy; Beer, Wine, Liquor; Tea, Coffee; Negative: Fried potatoes; High-fat meat; Processed meat; Fried Fish; Fried Poultry; Whole-Fat Dairy; Butter; Candy; Soft drinks; Bakery Desserts; Salty Snacks; Neutral: Potatoes; Fruit Juices; Refined grains; Eggs; Shellfish; Margarine; Chocolate & Diet Soft Drinks; Meal replacements; Pickled foods; Soups, Sugar substitutes
Djousse, 2018 ^40^ | DASH | Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened beverages (sodium not collected)
Fung, 2018 ^43^ | Food Group Index (FGI) | Positive: Vitamin A rich fruits and vegetables; Other fruits and vegetables; Legumes and nuts; Meat, poultry, fish; Eggs; Dairy; Grains, roots and tubers; Added fats/oils
Fung, 2018 ^43^ | Minimal Diet Diversity Score for Women (MDDW) | Positive: Vitamin A rich fruits and vegetables; Dark green, leafy vegetables; Other fruits and vegetables; Legumes and nuts; Meat, poultry, fish; Eggs; Dairy; Grains, roots and tubers
Fung, 2018 ^43^ | Prime Diet Quality Score (PDQS) | Positive: Vitamin A rich fruits and vegetables; Dark green, leafy vegetables; Carrots; Citrus fruits; Other fruits and vegetables; Legumes and nuts; Eggs; Dairy; Oils; Negative: Potatoes; Fried foods away from home; Sweets and ice cream; Sweetened beverage; Moderate: Meat, poultry, fish; Grains, roots and tubers
Glenn, 2021 ^47^ | Portfolio Diet Score | Positive: Plant protein (Soy beverage; green peas; refried beans; all other beans; tofu and textured vegetable products; bean soups); Viscous fiber (Oranges, grapefruit & tangerines, apples & pears, strawberries, okra, oats); (5) cooked cereals & grits); Nuts (Peanut butter, peanuts, other nuts and seeds); Phytosterols; MUFAs (Olive or canola oil; avocado and guacamole); Negative: Saturated fat (High fat dairy; eggs; chicken/turkey with skin; red and processed meats; organ meats; gravy; butter)
Goyal, 2021 ^48^ | DASH | Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Sodium
Gu, 2022 ^49^ | AHEI-2010 | Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol
Gu, 2022 ^49^ | PDQS | Positive: Dark leafy green vegetables, cruciferous vegetables, carrots, other vegetables, whole citrus fruits, other whole fruits, legumes, nuts, poultry, fish, eggs, whole grains, and liquid vegetable oils; Negative: Red meat, potatoes, processed meat, whole-milk dairy products, refined grains and baked goods, sugar-sweetened beverages, fried foods obtained away from home, and desserts and ice cream
Guasch-Ferré, 2022 ^50^ | AHEI-2010 | Positive: Vegetables (not potatoes, French fries); Fruit; Nuts and Soy Protein; Cereal Fiber; White: Red Meat Ratio; PUFA:SFA; Multi-Vitamin Use. Negative: Trans-UFA. Neutral: Alcohol
Kim, 2021 ^62^ | AHEI-2010 | Positive: Vegetables (not potatoes, French fries); Fruit; Nuts and Soy Protein; Cereal Fiber; White: Red Meat Ratio; PUFA:SFA; Multi-Vitamin Use. Negative: Trans-UFA. Neutral: Alcohol
Kim, 2021 ^62^ | DASH | Positive: Vegetables; Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Sodium
Kim, 2021 ^62^ | aMED | Positive: Vegetables; Legumes; Fruit, Nuts; Whole grains; Fish; MUFA/SFA. Negative: Red and Processed Meat; Neutral: Alcohol
Kong, 2021 ^63^ | AHEI-2010 | Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; Fatty Acids. Negative: Refined Grains; Added Sugars in “Empty Calories”; Solid Fats in “Empty Calories”; Sodium
Noel, 2020 ^74^ | AHEI-2010 | Positive: Vegetables (not potatoes, French fries); Fruit; Nuts and Soy Protein; Cereal Fiber; White: Red Meat Ratio; PUFA:SFA; Multi-Vitamin Use. Negative: Trans-UFA. Neutral: Alcohol
Rebholz, 2020 ^82^ | HEI-1990 | Positive: Vegetables; Fruit; Grains; Variety. Negative: Meat; Milk; Total Fat, SFA, Cholesterol. Neutral: Sodium
Rebholz, 2020 ^82^ | AHEI-2000 | Positive: Vegetables (not potatoes, French fries); Fruit; Nuts and Soy Protein; Cereal Fiber; White: Red Meat Ratio; PUFA:SFA; Multi-Vitamin Use. Negative: Trans-UFA. Neutral: Alcohol
Rebholz, 2020 ^82^ | HEI-2005 | Positive: Total Vegetables; Dark Green/Orange Vegetables, Legumes; Total Fruit; Whole Fruit; Whole Grains; Total Grains; Meat and Beans; Milk, Yogurt, Cheese, and Soy Beverages; Healthy Oils. Negative: SFA; Solid fats, Alcohol, and Added Sugars; Sodium
Rebholz, 2020 ^82^ | AHEI-2010 | Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol
Rebholz, 2020 ^82^ | HEI-2010 | Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; Fatty Acids. Negative: Refined Grains; Added Sugars in “Empty Calories”; Solid Fats in “Empty Calories”; Sodium
Rebholz, 2020 ^82^ | HEI-2015 | Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; PUFA+MUFA/SFA. Negative: Refined Grains; Added Sugars; SFA; Sodium
Shan, 2020 ^90^ | HEI-2015 | Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; PUFA+MUFA/SFA. Negative: Refined Grains; Added Sugars; SFA; Sodium
Shan, 2020 ^90^ | aMED | Positive: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA/SFA. Negative: Red and Processed Meat. Neutral: Alcohol
Shan, 2020 ^90^ | hPDI | Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Negative: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods
Shan, 2020 ^90^ | AHEI | Positive: Vegetables (not potatoes, French fries); Fruit; Nuts and Soy Protein; Cereal Fiber; White: Red Meat Ratio; PUFA:SFA; Multi-Vitamin Use. Negative: Trans-UFA. Neutral: Alcohol
Sotos-Prieto, 2015 ^96^ | aMED | Positive: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA/SFA. Negative: Red and Processed Meat. Neutral: Alcohol
Sotos-Prieto, 2015 ^96^ | AHEI-2010 | Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol
Sotos-Prieto, 2015 ^96^ | DASH | Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Sodium
Tsivgoulis, 2015 ^101^ | MDS | Positive: Vegetables; Legumes; Fruit; Cereals; Fish; MUFA/SFA. Negative: Red and Processed Meat; Dairy Products. Neutral: Alcohol
Tsivgoulis, 2015 ^101^ | AHEI-2010 | Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol
Tsivgoulis, 2015 ^101^ | aMED | Positive: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA/SFA. Negative: Red and Processed Meat. Neutral: Alcohol
Tsivgoulis, 2015 ^101^ | hPDI | Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Negative: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods
Tsivgoulis, 2015 ^101^ | DASH | Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low fat dairy; Negative: Red and Processed Meat; Sweetened beverages; Sodium;
Tsivgoulis, 2015 ^101^ | Diabetes Risk Reduction Diet (DRRD) | Positive: Fruit, Cereal Fiber, Nuts, Coffee, PUFA/SFA; Negative: Red meat, SSB and fruit juices, Trans Fat, Glycemic Index
Tsivgoulis, 2015 ^101^ | WCRF | Positive: Vegetables and Fruit; Dietary Fiber. Negative: Red and Processed Meat; Sugary Drinks; Alcohol; Sodium; Energy-Dense Foods
Tsivgoulis, 2015 ^101^ | Empirical Dietary Index for Hyperinsulinaemia (EDIH) | Positive: Processed meat, potatoes, low energy carbonated drinks and eggs; Inverse: Beer, wine, coffee, snacks, fruit juice, nuts, sweets desserts, oil and vinegar salad dressing, and mayonnaise and other creamy salad dressings
Tsivgoulis, 2015 ^101^ | Empirical Dietary Inflammatory Pattern (EDIP) | Positive: Processed meat, red meat, potatoes, low energy carbonated drinks, margarine and eggs; Inverse: Dark yellow vegetables, leafy green vegetables, beer, wine, liquor, coffee, oil and vinegar salad dressing, pizza, sweets desserts, snacks, condiments and fruit juice
Xu,2020 ^110^ | HEI-2015 | Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; PUFA+MUFA/SFA. Negative: Refined Grains; Added Sugars; SFA; Sodium
Xu,2020 ^110^ | AHEI-2010 | Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol
Zhong, 2021 ^115^ | AHEI-2010 | Positive: Fruit, Vegetable, Whole grain, Nuts and legume, Energy from PUFA, EPA+DHA; Moderate: Alcohol; Negative: Sweetened beverages, Red or processed meat, Energy from trans fat, Sodium
Kim, 2020 ^61^ | Plant-Based Diet Index (PDI) | Positive: Vegetables; Potatoes; Legumes; Fruit; Fruit Juices; Nuts; Whole Grains; Refined Grains; Tea and Coffee; Sugar-Sweetened and Artificially Sweetened Beverages; Sweets and Desserts. Negative: Fish or Seafood; Meat; Egg; Miscellaneous Animal Foods; Dairy; Animal Fat
Kim, 2020 ^61^ | hPDI | Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Negative: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods
Kim, 2020 ^61^ | Unhealthy Plant-Based Diet Index (uPDI) | Negative: Whole grains; Fruits; Vegetables; Nuts; Legumes; Vegetable oils; Tea/coffee; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; Positive: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts
Kim, 2020 ^61^ | Provegetarian Dietary Pattern Index | Positive: Whole grains, Refined grains; Vegetables; Potatoes; Legumes; Fruit; Nuts. Negative: Fish and Other Seafood; Meat; Eggs; Dairy; Animal Fats
Kim, 2020 ^61^ | PDI-Rotterdam | Positive: Whole grains; Fruits; Vegetables; Nuts; Legumes; Coffee and tea; Vegetable oil (including margarine); Refined grain; Potatoes; Total SSB (Fruit juice; SSB); Sweets and desserts; Alcoholic beverage; Negative: Animal fat; Egg; Dairy; Fish or seafood; Meat
Santiago-Torres, 2021 ^85^ | aMED | Positive: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA/SFA. Negative: Red and Processed Meat. Neutral: Alcohol
Santiago-Torres, 2021 ^85^ | DASH | Positive: Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Sodium
Santiago-Torres, 2021 ^85^ | HEI-2010 | Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; Fatty Acids. Negative: Refined Grains; Added Sugars in “Empty Calories”; Solid Fats in “Empty Calories”; Sodium
Santiago-Torres, 2021 ^85^ | MDS | Positive: Vegetables; Fruit, Nuts and legumes; Cereals; Fish; Whole grains; Meat; Dairy Products; MUFA/SFA; Neutral: Alcohol
Santiago-Torres, 2021 ^85^ | Traditional Mexican Diet (MexD) | Positive: Corn tortillas; Beans; Soups; Mexican-mixed dishes; Vegetables; Whole fruits; Rice; Full-fat milk & Mexican dishes; Negative: Oils; Solid fats and added sugars; Processed meats; Refined grains
Steffen, 2014 ^98^ | Modified MDS (mMDS) | Whole grain products; fruit; vegetables; fruit+vegetable juice; legumes; nuts; poultry; fish; eggs; coffee and tea; MUFA+PUFA/SFA ratio; Negative: Red and processed meat; dairy products; fried vegetables; refined grain; sauces; snack foods (cake, cookies, pie, pastry, crackers, granola bars, snack chips, and popcorn); candy; sugar group (sugar, honey, syrup, jam&jelly, sweet sauces); sweetened beverages; diet beverages; Neutral: Alcohol
Ahmad, 2018 ^21^ | Traditional Mediterranean Diet (tMED) | Positive: Vegetables (not potatoes); Legumes; Fruit and Nuts; Whole grains; Fish; MUFA/SFA. Negative: Red and Processed Meat; Dairy Products. Neutral: Alcohol
Choi, 2022 ^34^ | APDQS | Positive: Vegetables-Green; Vegetables-Yellow; Vegetables-Other; Tomatoes; Beans/Legumes; Fruit; Avocado; Nuts, Seeds; Soy Products; Whole Grains; Fish; Lean fish; Poultry; Low-Fat Dairy; Vegetable Oil; Beer, Wine, Liquor; Tea, Coffee; Negative: Fried potatoes; High-fat meat; Processed meats; Organ meats; Fried Fish/Poultry; High-Fat Dairy; Pastries; Sweets; Desserts; Sugar-sweetened soft drinks; Butter; Fried Foods; Salty Snacks; Sauces; Neutral: Potatoes; Fruit Juices; Refined grains; Eggs; Shellfish; Lean meat; Margarine; Chocolate & Diet Soft Drinks; Meal replacements; Pickled foods; Sugar substitutes; Diet drinks
Chomistek, 2015 ^36^ | AHEI-2010 | Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium; Moderate: Alcohol
Fung, 2016 ^44^ | Food Quality Score (FQS) | Positive: Vegetables,Fruit, Nuts and Legumes, Whole grains, Yogurt; Coffee; Negative: Red meats; Processed Meats; Desserts and ice cream; Refined grains; Potatoes; Potato chips; Fried foods prepared away from home; Sugar-sweetened Beverages
Hu, 2019 ^52^ | AHEI-2010 | Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: alcohol
Hu, 2019 ^52^ | aMED | Positive: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA/SFA. Negative: Red and Processed Meat. Neutral: alcohol
Hu, 2019 ^52^ | DASH | Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened beverages; Sodium
Hu, 2019 ^52^ | HEI-2015 | Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; PUFA+MUFA/SFA. Negative: Refined Grains; Added Sugars; SFA; Sodium
Neuhouser, 2023 ^73^ | HEI-2010 | Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; Fatty Acids. Negative: Refined Grains; Added Sugars in “Empty Calories”; Solid Fats in “Empty Calories”; Sodium
Kim, 2019 ^58^ | PDI | Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Negative: Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods
Kim, 2019 ^58^ | hPDI | Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Negative: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods
Kim, 2019 ^58^ | uPDI | Negative: Whole grains; Fruits; Vegetables; Nuts; Legumes; Vegetable oils; Tea/coffee; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; Positive: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts
Kim, 2019 ^58^ | Pro-vegetarian Diet Index | Grains, fruits, vegetables, nuts, legumes, and potatoes, animal fat, dairy, eggs, fish or seafood, meat
Cheng, 2018 ^32^ | mMDS | Positive: Vegetables (not potatoes), Fruits, Whole grains, Legumes, Fish, Nuts, MUFA:SFA; Negative: Red and processed meats; Other: Alcohol
Cheng, 2018 ^32^ | Evolutionaryconcordance (ECL) diet score | Positive: Vegetables, Fruits, Lean meats, Fish, Nuts, Fruit and vegetable diversity, Calcium; Negative: Red and processed meats, Sodium, Dairy foods, Grains and starches, Baked goods, SSB, Alcohol
Baden, 2019 ^23^ | PDI | Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Negative: Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods
Baden, 2019 ^23^ | hPDI | Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Negative: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods
Baden, 2019 ^23^ | uPDI | Negative: Whole grains; Fruits; Vegetables; Nuts; Legumes; Vegetable oils; Tea/coffee; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; Positive: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts
Li, 2022 ^65^ | PDI | Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Negative: Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods
Li, 2022 ^65^ | hPDI | Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Negative: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods
Li, 2022 ^65^ | uPDI | Negative: Whole grains; Fruits; Vegetables; Nuts; Legumes; Vegetable oils; Tea/coffee; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; Positive: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts
Baden, 2021 ^24^ | PDI | Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Negative: Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods
Baden, 2021 ^24^ | hPDI | Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Negative: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods
Baden, 2021 ^24^ | uPDI | Negative: Whole grains; Fruits; Vegetables; Nuts; Legumes; Vegetable oils; Tea/coffee; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; Positive: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts
Musicus, 2022 ^71^ | AHEI-2010 | Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium (note: alcohol excluded)
Musicus, 2022 ^71^ | PDI | Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Negative: Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods
Musicus, 2022 ^71^ | hPDI | Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Negative: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods
Musicus, 2022 ^71^ | uPDI | Negative: Whole grains; Fruits; Vegetables; Nuts; Legumes; Vegetable oils; Tea/coffee; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; Positive: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts
Satija, 2017 ^86^ | PDI | Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Negative: Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods
Satija, 2017 ^86^ | hPDI | Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Negative: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods
Satija, 2017 ^86^ | uPDI | Negative: Whole grains; Fruits; Vegetables; Nuts; Legumes; Vegetable oils; Tea/coffee; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; Positive: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts
Kauffman, 2020 ^56^ | AHEI-2010 | Positive: Vegetables (not potatoes, French fries); Fruit; Nuts and Soy Protein; Cereal Fiber; White: Red Meat Ratio; PUFA:SFA; Multi-Vitamin Use. Negative: Trans-UFA. Neutral: Alcohol
Zhong, 2021 ^114^ | UPF, NOVA Classification System | Positive: soft drinks (diet/caffeinated, regular/caffeinated, diet/decaffeinated, regular/decaffeinated), cereals (Hot dogs, turkey/low fat; Hot dogs, regular; English muffins and bagels; White bread/rolls; Corn bread/muffins; Biscuits; Quick breads; Donuts, sweet rolls, Danishes, and pop tarts; Pancakes, waffles, and French toast; Ready-to-eat cereal (highly fortified); Ready-to-eat cereal (other); Cookies and brownies; Cakes (low fat); Cakes (regular); Pies, cream/custard/other; Pies, fruit; Pies, pecan; Pies, pumpkin/sweet potato; Lasagna, ravioli, shells; Macaroni and cheese; Pizza without meat); ultraprocessed fruits and vegetables (Fried potatoes; Potato salad; Fruit drinks, diet; Fruit drinks, regular), ultra-processed dairy products (Sour cream, low fat; Sour cream, regular; Cream cheese, low fat; Cream cheese, regular; Ice cream/ice milk, low fat; Regular ice cream; Frozen yogurt, ices, and sorbet; Creamed soups), meat and fish (Restaurant or industrial hamburgers; Fried chicken, dark meat/no skin; Fried chicken, dark meat/with skin; Fried chicken, white meat/no skin; Fried chicken, white meat/with skin; Fried fish, fat added; Pizza with meat), sauces and dressings (Gravy; Salad dressing, low fat on salad and vegetables; Salad dressing, nonfat on salad and vegetables; Salad dressing, regular on salad and vegetables; Mayonnaise, diet on salad; Mayonnaise, fat free on salad; Mayonnaise, regular on salad; Mayonnaise, diet on sandwich; Mayonnaise, fat free on sandwich; Mayonnaise, regular on sandwich), salty snacks (Crackers; Potato/corn/other chips; Potato/corn/other chips-low fat; Popcorn), sugary products (Candy, chocolate; Candy, not chocolate; Saccharine in coffee and tea), and margarine (Margarine, diet; Margarine, fat free; Margarine, regular; Margarine, diet on bread)
Du, 2021 ^41^ | UPF, NOVA Classification System Group 4 | Positive: Dairy products (ice cream; fats and oils: margarine); Meats (hamburgers, hot dogs, processed meats (sausage, salami, bologna), beef, pork, or lamb in dishes); Sugary products (chocolate bars or pieces (Hershey’s, plain M&M’s, Snickers, Reese’s), candy without chocolate); Bakery goods (ready-made pie, donuts, biscuits, or cornbread); Danish pastry, sweet roll, coffee cake, croissant, cookies, cake, or brownie; Cereals (cold breakfast cereal; fried foods: potato chips or corn chips, French fried potatoes, food fried away from home); Beverages (orange or grapefruit juice, low calorie and regular soft drinks, fruit-flavored punch or noncarbonated beverages (lemonade, Kool-Aid, Hawaiian Punch)); liquor: hard liquor.
Li, 2020 ^66^ | EDIP | Anti-inflammatory group: tea, coffee, dark yellow vegetables (carrots, or squash), leafy green vegetables (cabbage, spinach, or lettuce), snacks (cracker, or potato chips), fruit juice (apple juice, cantaloupe juice, orange juice, or other fruit juice), pizza Pro-inflammatory group: processed meat (sausage), red meat (beef, or lamb), organ meat (beef, calf, or chicken liver), other fish (canned tuna, or fish), other vegetables (mixed vegetables, green pepper, cooked mushroom, eggplant, zucchini, or cucumber), refined grains (white bread, biscuit, white rice, pasta, or vermicelli), highenergy and low energy beverages (cola with sugar, carbonated beverages with sugar, fruit punch drinks), and tomatoes
Pang, 2021 ^76^ | EDIP | Anti-inflammatory group: tea, coffee, dark yellow vegetables (carrots, or squash), leafy green vegetables (cabbage, spinach, or lettuce), snacks (cracker, or potato chips), fruit juice (apple juice, cantaloupe juice, orange juice, or other fruit juice), pizza Pro-inflammatory group: processed meat (sausage), red meat (beef, or lamb), organ meat (beef, calf, or chicken liver), other fish (canned tuna, or fish), other vegetables (mixed vegetables, green pepper, cooked mushroom, eggplant, zucchini, or cucumber), refined grains (white bread, biscuit, white rice, pasta, or vermicelli), highenergy and low energy beverages (cola with sugar, carbonated beverages with sugar, fruit punch drinks), and tomatoes
Juul, 2021 ^55^ | UPF, NOVA Classification System | Positive: Nondairy coffee whitener, ice cream, sherbet/ice milk, margarine, red chili sauce, hot dogs, hamburger, processed meats, cold breakfast cereals, commercially baked cookies, pies, and sweet rolls, doughnuts, brownies, breads, English muffins/bagels, muffins/biscuits, pancakes/waffles, French fries, chips, crackers, pizza, sugar-sweetened and low-calorie carbonated beverages, punch/lemonade, liquor, chocolate, candy bars, candy without chocolate, popcorn, fried food away from home, meat sandwiches, yoghurt.
Bertoia, 2014 ^25^ | MDS | Positive: Vegetables; Fruit, Nuts and legumes; Cereals; Fish; Whole grains; MUFA/SFA. Negative: Red and Processed Meat; Poultry; high-fat dairy. Neutral: Alcohol
Bertoia, 2014 ^25^ | DASH | Positive: Vegetables; Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Sodium
George, 2021 ^46^ | HEI-2015 | Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; PUFA+MUFA/SFA. Negative: Refined Grains; Added Sugars; SFA; Sodium
Inoue-Choi, 2022 ^53^ | HEI-2015 | Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; PUFA+MUFA/SFA. Negative: Refined Grains; Added Sugars; SFA; Sodium
Keaver, 2021 ^57^ | Comprehensive Diet Quality Index (cDQI) | Positive: Whole grains, vegetables excluding white potatoes, whole fruits, nuts/seeds/legumes, vegetable oils and coffee/tea, fish/seafood, dairy products and poultry; Negative: Refined grains, fruit juices, sugar-sweetened beverages and sweets/desserts, processed meats, unprocessed red meats and eggs
Keaver, 2021 ^57^ | Plant-based Diet Quality Index (pDQI) | Positive: Whole grains, vegetables excluding white potatoes, whole fruits, nuts/seeds/legumes, vegetable oils and coffee/tea; Negative: Refined grains, fruit juices, sugar-sweetened beverages and sweets/desserts
Keaver, 2021 ^57^ | Animal-based Diet Quality Index (aDQI) | Positive: Fish/seafood, dairy products and poultry; Negative: processed meats, unprocessed red meats and eggs
Kim, 2018 ^59^ | PDI | Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Negative: Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods
Kim, 2018 ^59^ | hPDI | Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Negative: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods
Kim, 2018 ^59^ | uPDI | Negative: Whole grains; Fruits; Vegetables; Nuts; Legumes; Vegetable oils; Tea/coffee; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; Positive: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts
Kim 2019 ^60^ | UPF, NOVA Classification System | Positive: Chocolate milk, ice cream, ice milk, milkshakes, bacon, sausage, processed meats, sweetened cereals, spaghetti/pasta with tomato sauce, cheese dishes, pizza, calzone, lasagna, salted snacks, cakes, cookies, brownies, fruit juices, sugarsweetened and artificially sweetened beverages (HiC, Tang, Koolaid, diet colas, diet sodas, regular colas and sodas), hard liquor, margarine
Park, 2016 ^79^ | Mediterranean Dietary Score (MedDietScore) | Positive: Vegetables; Legumes; Fruit; Whole Grains; Fish; MUFA:SFA. Negative: Red and Processed Meat; Poultry; Dairy products; alcohol
Shah, 2018 ^88^ | MDS | Positive: Vegetables; Legumes; Fruit, Nuts; Cereals; Fish; MUFA/SFA. Negative score component: Red and Processed Meat; Dairy Products. Neutral: alcohol
Shah, 2018 ^88^ | DASH | Positive: Vegetables; Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Added sugar; Sodium
Shikany, 2021 ^93^ | MDS | Positive: Vegetables; Legumes; Fruit; Cereals; Fish; MUFA/SFA. Negative: Meat; Dairy Products. Neutral: Alcohol
Troeschel, 2021 ^100^ | ECL- dietary component | Positive: Vegetables, Fruits, Lean meats, Fish, Nuts, Fruit/vegetable diversity, calcium; Negative: Red/processed meats, Dairy products, Grains, Baked goods, SSB, Sodium
Booth, 2016 ^27^ | MDS | Positive: Vegetables; Legumes; Fruit, Nuts; Cereals; Fish; MUFA/SFA. Negative score component: Red and Processed Meat; Dairy Products. Neutral: Alcohol
Campos, 2019 ^28^ | DASH | Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Sodium
Chang, 2022 ^29^ | DASH | Positive: Total vegetables; Legumes/Beans; Total fruits; Total Grains; Negative: Total red meat, poultry, fish; Total dairy products; Sugar/sweets/pastries; E% from fat E% saturated fat; Sodium
Del Gobbo, 2015 ^39^ | AHEI-2010 | Positive: Vegetables (not potatoes, French fries); Fruit; Nuts and Soy Protein; Cereal Fiber; White: Red Meat Ratio; PUFA:SFA; Multi-Vitamin Use. Negative: Trans-UFA. Neutral: Alcohol
Del Gobbo, 2015 ^39^ | DASH | Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Sodium
Schrauben, 2021 ^87^ | American Heart Association (AHA) dietary score | Positive: Fruits and vegetables, fish, whole grains; Negative: sodium, sugarsweetened beverages; Neutral/Moderate: Alcohol
Weston, 2022 ^108^ | PDI | Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Negative: Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods
Weston, 2022 ^108^ | hPDI | Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Negative: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods
Weston, 2022 ^108^ | uPDI | Negative: Whole grains; Fruits; Vegetables; Nuts; Legumes; Vegetable oils; Tea/coffee; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; Positive: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts
Bhupathiraju, 2022 ^26^ | PDI | Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Negative: Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods
Bhupathiraju, 2022 ^26^ | hPDI | Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Negative: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods
Bhupathiraju, 2022 ^26^ | uPDI | Negative: Whole grains; Fruits; Vegetables; Nuts; Legumes; Vegetable oils; Tea/coffee; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; Positive: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts
Mattei, 2017 ^69^ | AHA Dietary Score | Positive: Vegetables and Fruit; Variety; Whole Grains; Fish; Negative: SFA; Total fats; Trans Fat; Cholesterol; Added Sugars; Sodium; Neutral: Alcohol
Mattei, 2017 ^69^ | AHEI-2010 | Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol
Mattei, 2017 ^69^ | HEI-2005 | Positive: Total Vegetables; Dark Green/Orange Vegetables, Legumes; Total Fruit; Whole Fruit; Whole Grains; Total Grains; Meat and Beans; Milk, Yogurt, Cheese, and Soy Beverages; Healthy Oils. Negative: SFA; Solid fats, Alcohol, and Added Sugars; Sodium
Mattei, 2017 ^69^ | MDS | Positive: Vegetables; Legumes (and beans); Fruit (and Orange juice); Whole grains (oatmeal); Fish (traditional); MUFA/SFA (corn oil). Negative: Red and Processed Meat; Dairy Products (Whole Milk). Neutral: Alcohol (Beer)
Mattei, 2017 ^69^ | DASH | Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Total dairy; Negative: Red and Processed Meat; Sweetened beverages; Sodium;
Rai, 2023 ^81^ | South-Asian Mediterranean-style (SAM) diet score | Positive: Vegetables, fruits, legumes, nuts, whole grains, fish, and monounsaturated to saturated fat ratio; Moderation: Alcohol (5 g/d to 25 g/d); Negative: Red/processed meats
Weng, 2013 ^107^ | Healthy Food Score (HFS) | Positive: Vegetables; Fruit (without juice); Fruit juice; Legumes; Nuts; Whole Grains; Refined grain; Dairy (combined low-fat and high fat milk, cheese, yogurt, ice cream); Fish; Coffee and tea; Negative: Meat (combined poultry, processed meat, beef, pork, and lamb); Diet beverages; Sugar-sweetened beverages; Neutral: alcohol
Cuenca-Garcia, 2014 ^37^ | Ideal Diet Index (IDI) | Positive: Vegetables and Fruit; Legumes, Nuts, and Seeds; Whole Grains; Fish. Negative: Processed Meat; Added Sugar; SFA; Sodium
Cuenca-Garcia, 2014 ^37^ | DQI | Positive: Vegetables and Fruit; Breads, Cereal, and Legumes; Calcium. Negative: Total Fat; SFA; Cholesterol; Protein; Sodium
Cuenca-Garcia, 2014 ^37^ | MDS | Positive: Vegetables; Legumes; Fruit, Nuts; Cereals; Fish; MUFA/SFA. Negative: Red and Processed Meat; Dairy Products. Neutral: Alcohol
Jiang, 2015 ^128^ | DASH | Positive: Vegetables; Nuts, Seeds and Legumes; Fruit; Total Grains; Whole Grains; Low-Fat Dairy; Negative: Fish; Meat; Poultry; Sweets; Total fat; Saturated fat ; Sodium;
Buijsse, 2015 ^127^ | APDQS | Positive: Vegetables-Green; Vegetables-Yellow; Vegetables-Other; Tomatoes; Beans/Legumes; Fruit; Avocado; Nuts, Seeds; Soy Products; Whole Grains; Fish; Lean fish; Poultry; Low-Fat Dairy; Vegetable Oil; Beer, Wine, Liquor; Tea, Coffee. Negative: Fried potatoes; High-fat meat; Processed meats; Organ meats; Fried Fish/Poultry; High-Fat Dairy; Pastries; Sweets; Desserts; Sugar-sweetened soft drinks; Butter; Fried Foods; Salty Snacks; Sauces. Neutral: Potatoes; Fruit Juices; Refined grains; Eggs; Shellfish; Lean meat; Margarine; Chocolate & Diet Soft Drinks; Meal replacements; Pickled foods; Sugar substitutes; Diet drinks
Li, 2016 ^126^ | AHEI-2010 | Positive: Vegetables (not potatoes, French fries); Fruit; Nuts and Soy Protein; Cereal Fiber; White: Red Meat Ratio; PUFA:SFA; Multi-Vitamin Use. Negative: Trans-UFA. Neutral: Alcohol
Li, 2016 ^126^ | MDS | Positive: Vegetables; Legumes; Fruit; Nuts; Cereals; Fish; MUFA/SFA; Negative: Red and Processed Meat; Dairy Products. Neutral: Alcohol
Li, 2016 ^126^ | DASH | Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Sodium
Whelton, 2015 ^125^ | MDS | Positive: Vegetables; Legumes; Fruit; Nuts; Cereals; Fish; MUFA/SFA. Negative: Red and Processed Meat; Dairy Products. Neutral: Alcohol
Thomas, 2018 ^124^ | DASH | Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Sodium
Wang, 2024 ^104^ | EDIH | Positive: Processed meat, potatoes, low energy carbonated drinks and eggs; Inverse: Beer, wine, coffee, snacks, fruit juice, nuts, sweets desserts, oil and vinegar salad dressing, and mayonnaise and other creamy salad dressings
Wang, 2024 ^104^ | Empirical Dietary Index for Insulin Resistance (EDIR) | Positive: Processed meat, red meat, potatoes, low energy carbonated drinks, margarine and eggs; Inverse: Dark yellow vegetables, leafy green vegetables, beer, wine, liquor, coffee, oil and vinegar salad dressing, pizza, sweets desserts, snacks, condiments and fruit juice
Factor/Cluster Analysis^*^; * A posteriori dietary pattern
Liese, 2021 ^68^ | Cluster 1 | Best diet quality, exceeding fruit goals, low dairy
Liese, 2021 ^68^ | Cluster 2 | Second best diet quality, exceeding fruit + sodium goals
Liese, 2021 ^68^ | Cluster 3 | Dairy adherers, greens & beans avoidance
Liese, 2021 ^68^ | Cluster 4 | Exceeding greens & beans, fruit and vegetables
Liese, 2021 ^68^ | Cluster 5 | Lowest rank diet, exceeding seafood & plant protein
Shikany, 2021 ^93^ | “Convenience” | High factor loading on mixed dishes, pasta dishes, pizza, Mexican food, and Chinese food
Shikany, 2021 ^93^ | “Plant-based” | High factor loading on vegetables, fruits, fruit juice, cereal, beans, fish, poultry, and yogurt
Shikany, 2021 ^93^ | “Sweets” | High factor loading on added sugars, desserts, chocolate, candy, and sweetened breakfast foods
Shikany, 2021 ^93^ | “Southern” | High factor loading on added fats, fried food, eggs and egg dishes, organ meats, processed meats, and sugar-sweetened beverages
Shikany, 2021 ^93^ | “Alcohol and Salad” | High factor loading on beer, wine, liquor, green leafy vegetables, tomatoes, and salad dressing
Tharrey, 2018 ^99^ | “Grains” | Positive: grains, other vegetables, potatoes. Negative: seafood, poultry, and yogurt
Tharrey, 2018 ^99^ | “Processed Foods” | Positive: cheese, animal fat, eggs, potatoes, milk. Negative: soy
Tharrey, 2018 ^99^ | “Meat” | Positive: red meat, processed meat, poultry, seafood. Negative: grains, yogurt, and soy
Tharrey, 2018 ^99^ | “Legumes, Fruits, and Vegetables” | Positive: potatoes, vegetables, legumes, fruits. Negative: milk
Tharrey, 2018 ^99^ | “Nuts and Seeds” | Positive: peanuts, treenuts and seeds, seafood. Negative: eggs, poultry
Judd, 2013 ^54^ | “Convenience” | Positive: Beans; Chinese food; Condiments; Desserts; Fish; Fried food; Fried potatoes; High fat dairy; Mexican dishes; Mixed dishes with meat; Organ meat; Pasta dishes; Pizza; Potatoes; Poultry; Processed meats; Red meat; Refined grains; Salty snacks; Shell fish; Soup; Sweet breakfast foods; Vegetables -green leafy; Vegetable mixed dishes
Judd, 2013 ^54^ | “Healthy” | Positive: 100% fruit juice; Beans; Bread - Whole Grain; Cereal; Cereal-high fiber; Fish; Fruit; Lowfat dairy; Milk alternatives; Milk - Lowfat; Poultry; Refined grains; Salad dressing/sauces; Seeds, nuts; Soup; Vegetable - cruciferous; Vegetable - dark yellow; Vegetable - green leafy; Vegetable - other; Vegetable - tomato; Vegetable mixed dishes; Water; Yogurt; Negative: Alcohol (Beer); Pizza; Soda
Judd, 2013 ^54^ | “Sweets/Fats” | Positive: Added fats; Bread; Bread - Whole Grain; Butter; Candy; Chocolate; Coffee; Condiments; Desserts; Fried potatoes; Highfat dairy; Margarine; Milk - Highfat; Miscellaneous sugar; Pasta dishes; Pizza; Potatoes; Processed meats; Red meat; Refined grains; Salty snacks; Seeds, nuts; Sweet breakfast foods; Tea
Judd, 2013 ^54^ | “Southern” | Positive: 100% fruit juice; Added fats; Bread; Egg and egg dishes; Fried food; Fried potatoes; Milk - Highfat; Miscellaneous sugar; Organ meat; Processed meats; Red meat; Refined grains; Shell fish; Soda; SSB Negative: Cereal-high fiber; Coffee; Lowfat dairy; Milk - Lowfat; Vegetable - green leafy; Yogurt
Judd, 2013 ^54^ | “Alcohol/salads” | Positive: Added fats; Beer; Butter; Coffee; Eggs and egg dishes; Fish; Condiments; High fat dairy; Liquor; Processed meats; Red meat; Salad dressing/sauces; Seeds, nuts; Shellfish; Vegetable - green leafy; Vegetable - tomato; Alcohol (Wine); Negative: 100% fruit juice; Cereal; Desserts; Sugar-sweetened beverages; Vegetable - dark yellow; Vegetable mixed dishes
Lara, 2019 ^64^ | “Convenience” | Meat dishes, pasta, Mexican dishes, pizza, fried potatoes, Chinese dishes and fast food
Lara, 2019 ^64^ | “Plant-based” | Cruciferous vegetables and other vegetables, fruit, beans, and fish
Lara, 2019 ^64^ | “Sweets/Fats” | Desserts, bread, sweet breakfast foods, chocolate, candy, solid fats and oils, and miscellaneous sugar
Lara, 2019 ^64^ | “Southern” | Fried food, organ meats, processed meats, eggs, added fats, and sugar-sweetened beverages
Lara, 2019 ^64^ | “Alcohol/Salads” | Wine, liquor, beer, leafy greens and salad dressing
Ogilvie, 2017 ^75^ | “Western” | Positive: Processed meats, fried food, refined grains, red meat, eggs, dessert, highfat dairy, sugar-sweetened beverages, fat, sweets, legumes, potatoes, ice cream, other vegetables, nuts & peanut butter, coffee, tomatoes, tea, dark-leaf vegetables, carotene vegetables; Negative: Diet soda, fish & seafood, poultry, cruciferous vegetables, fruits (excluding fruit juice), whole grains, low-fat dairy, yogurt; Neutral: Fruit juice
Ogilvie, 2017 ^75^ | “Healthy” | Positive: Cruciferous vegetables, fruits (excluding fruit juice), carotene vegetables, other vegetables, fish & seafood, poultry, dark-leaf vegetables, whole grains, tomatoes, legumes, low-fat dairy, yogurt, fruit juice, potatoes, nuts & peanut butter, fat, diet soda, tea, high-fat dairy, red meat, dessert, ice cream; Negative: Sweets, eggs, coffee, processed meat, refined grains, fried food, sugar-sweetened beverages
Shikany, 2015 ^92^ | “Convenience” | Positive: Beans; Chinese food; Condiments; Desserts; Fish; Fried food; Fried potatoes; High fat dairy; Mexican dishes; Mixed dishes with meat; Organ meat; Pasta dishes; Pizza; Potatoes; Poultry; Processed meats; Red meat; Refined grains; Salty snacks; Shell fish; Soup; Sweet breakfast foods; Vegetables -green leafy; Vegetable mixed dishes
Shikany, 2015 ^92^ | “Plant-based” | Positive: 100% fruit juice; Beans; Bread - Whole Grain; Cereal; Cereal-high fiber; Fish; Fruit; Lowfat dairy; Milk alternatives; Milk - Lowfat; Poultry; Refined grains; Salad dressing/sauces; Seeds, nuts; Soup; Vegetable - cruciferous; Vegetable - dark yellow; Vegetable - green leafy; Vegetable - other; Vegetable - tomato; Vegetable mixed dishes; Water; Yogurt; Negative: Alcohol (Beer); Pizza; Soda
Shikany, 2015 ^92^ | “Sweets/Fats” | Positive: Added fats; Bread; Bread - Whole Grain; Butter; Candy; Chocolate; Coffee; Condiments; Desserts; Fried potatoes; Highfat dairy; Margarine; Milk - Highfat; Miscellaneous sugar; Pasta dishes; Pizza; Potatoes; Processed meats; Red meat; Refined grains; Salty snacks; Seeds, nuts; Sweet breakfast foods; Tea
Shikany, 2015 ^92^ | “Southern” | Positive: 100% fruit juice; Added fats; Bread; Egg and egg dishes; Fried food; Fried potatoes; Milk - Highfat; Miscellaneous sugar; Organ meat; Processed meats; Red meat; Refined grains; Shell fish; Soda; SSB Negative: Cereal-high fiber; Coffee; Lowfat dairy; Milk - Lowfat; Vegetable - green leafy; Yogurt
Shikany, 2015 ^92^ | “Alcohol/Salads” | Positive: Added fats; Beer; Butter; Coffee; Eggs and egg dishes; Fish; Condiments; Highfat dairy; Liquor; Processed meats; Red meat; Salad dressing/sauces; Seeds, nuts; Shell fish; Vegetable - green leafy; Vegetable - tomato; Alcohol (Wine); Negative: 100% fruit juice; Cereal; Desserts; Sugar-sweetened beverages; Vegetable - dark yellow; Vegetable mixed dishes
Wang, 2020 ^103^ | “Western” (PCA) | High: Dairy products, Pizza, Unprocessed red meat, Processed red meat, Salad dressings; Low: Fruits, Milk with lower fat content, Legumes, Cruciferous vegetables, Tomatoes
Wang, 2020 ^103^ | “Prudent” (PCA) | High: Dark-yellow vegetables, Green leafy vegetables, Cruciferous vegetables, Legumes, Fruits; Low: Whole milk, Margarine, Sweets and desserts, Organ meat, Beer
Wang, 2020 ^103^ | “Western” (RRR) | High: Margarine, Fried fish, Artifically sweetened beverages, Processed red meat, Sugar-sweetened beverages; Low: Soup, Fiber cereals, Fruits, Cruciferous vegetables, Wine
Wang, 2020 ^103^ | “Western” (PLS) | High: French fries, Processed red meat, Fried fish, Margarine, Sugar-Sweetened beverages; Low: Fruits, Legumes, Dark-yellow vegetables, Cruciferous vegetables, Soup
Nazari, 2018 ^72^ | RRR | Positive: Fats and oils; Poultry; Non-diet soda; Processed meat; Tomatoes; Legumes; Chicken, tuna, and egg salad; Friend potatoes; Negative: Dark-yellow vegetables; Cruciferous vegetables
Nazari, 2018 ^72^ | PCR | Positive: Red meat; High-fat cheeses and sauces; Poultry; White bread; Tomatoes; Fats and oils; Fried potatoes; Processed meat; Other vegetables; Potato and pasta salad
Nazari, 2018 ^72^ | PLS | Positive: Fats and oils; Processed meat; High-fat cheeses and sauces; Fried potatoes; Non-diet soda; Tomatoes; Desserts; Poultry; Negative: Cruciferous vegetables; Dark-yellow vegetables
Experimental Diet
Jeong, 2023 ^116^ | DASH | Positive: Fruits and vegetables (9.6 servings), fat-free or low fat dairy, whole grains, poultry, fish, nuts, seeds and legumes; Negative: Saturated and total fat, cholesterol, sweets and sugary beverages. Magnesium, Potassium and Calcium at 75th percentile of US consumption
Jeong, 2023 ^116^ | Fruits/Vegetables diet | Fruits and vegetables (8.5 servings), nuts, seeds and legumes; High in red meats. High in total fat, saturated fat and cholesterol. High in fiber. Potassium, Magnesium at 75% US consumption
Jeong, 2023 ^116^ | Control | Fruits and vegetables (3.6 servings), red meats, snacks, and sweets. High in total fat, saturated fat and cholesterol. Low in fiber. K, Mg, and Ca at 25th of US consumption
Juraschek, 2017 ^117^ | DASH | Positive: Fruits (5.2 servings), vegetables (4.4 servings), low-fat dairy (2.0 servings), regular fat dairy (0.7 servings), whole grains (7.5 servings), poultry (0.6 servings), fish (0.5 servings), nuts, seeds, legumes (0.7 servings); Negative: Red meat (beef, portk , ham - 0.5 servings), snacks and sweets (0.7 servings). SSB, reducted intake of saturated fat, total fat, cholesterol (fats, oils and salad dressings - 2.5 servings)
Juraschek, 2017 ^117^ | Control | Typical American diet - Fruits (1.6 servings), vegetables (2.0 servings), Grains (8.2 servings), Low-fat dairy (0.1 serving), Regular-fat dairy (0.4 serving), Nuts, seeds, and legumes (0.0 servings), Beef, pork, and ham (1.5 servings), Poultry (0.8 servings), Fish (0.2 servings), Fat, oils, and salad dressing (5.8 servings), snacks and sweets (4.1 servings)
Krishnan, 2018 ^118^ | DGA | Fruits (total): 2.3 cups (whole fruit 1.6 c, juice: 0.7 c); Vegetables (total): 3.4 cups (Dark green: 0.4, red and orange: 1.1, beans and peas: 0.3, starchy vegetables: 0.8, other vegetables: 0.9); Grains: 5.2 ounces (whole grain: 2.8; enriched refined grains: 2.4); Meat, fish, poultry, eggs, nuts and seeds ounces: 5.2 ounces (seafood: 1.1; Meat, poultry, eggs: 3.4; Nuts, seeds, soy products: 0.8); Dairy: 3.3 c; Oils, g: 33.1; Solid fats and added sugars, kcal: 333 (% of energy: 15)
Krishnan, 2018 ^118^ | TAD | Fruits (total): 1 cups (whole fruit 0.4 c, juice: 0.6 c); Vegetables (total): 1.5 cups (Dark green: 0.12 c, red and orange: 0.3 c, beans and peas: 0.1 c, starchy vegetables: 0.54 c, other vegetables: 0.5 c); Grains: 6.8 ounces (whole grain: 1.1; enriched refined grains: 5.7); Meat, fish, poultry, eggs, nuts and seeds ounces: 6.5 ounces (seafood: 0.6; Meat, poultry, eggs: 5.4; Nuts, seeds, soy products: 0.5); Dairy: 1.5 c; Oils, g: 22.4; Solid fats and added sugars, kcal: 757 (% of energy: 33)
Van Horn, 2021 ^123^ | Intervention | Reduce total fat to 20% of total energy intake; increase vegetable and fruit intake to ≥5 servings/d; and increase grain intake to ≥6 servings/d
Van Horn, 2021 ^123^ | Control | Printed health-related materials
Schroeder, 2015 ^120^ | Korean Diet | Grains (mix of whole and refined); meat, fish, eggs, and beans; vegetables; fruits; and milk and dairy products; Kimchi, fermented bean paste
Schroeder, 2015 ^120^ | DGA Diet | Positive: Vegetables, fruit, whole grains, fiber, seafood, lean meat, legumes and nuts, and low-fat dairy; Negative: sodium, saturated fat, refined grains
Schroeder, 2015 ^120^ | Typical American Diet | Positive: High in sodium, saturated fat, refined grains; Negative: Low in vegetables, fruit, whole grains, fiber, lean meats, and dairy
Prentice, 2019 ^119^ | Intervention | Reduction in fat from ~35% of energy at baseline to 20% energy+ increase in veg, fruits, grains; vegetables (2.6 cups), fruits (2.5 cups) and total grains (5.4 cups) - whole grain: 1.4 cups; other grains 4.0 cups
Prentice, 2019 ^119^ | Comparator | Written health-related materials; Veg (2.1 cups); fruits (1.8 cups); total grain (4.7 cups) - whole-grain: 1.1 cups; other grain: 3.6 cups
Sidahmed, 2014 ^121^ | “Healthy Eating” Arm | Fruit 2 serv/d, Vegetables 2 serv/d, Dark green or orange vegetables 1 serv/d, Whole grains ≥3 serv/d, SFA <10% Total E
Sidahmed, 2014 ^121^ | “Mediterranean” Arm | Fruit (vit. C) 1 serv/d, Fruit (Other) 1 serv/d, Allium vegetables 1-2 serv/d, Dark green vegetables 1-2 serv/d, Orange and yellow vegetables 1-2 serv/d, Red vegetables 1-2 serv/d, Other vegetables 1-2 serv/d, Dark green herbs 1 serv/d, Whole grains ≥3 serv/d, High MUFA foods 7-10 exchanges/d, High n-3 foods 3 oz, twice/wk
Tussing-Humphreys, 2022^122^ | Mediterranean Diet Group | Instruction to follow MedDiet Score recommendations. Increased MedDiet score from baseline to follow-up, higher score than Control Group at follow-up. MedDiet: Positive: Non-refined grains, potatoes, fruit, vegetables, legumes and nuts, fish, olive oil. Negative: Red and processed meat, poultry, full-fat dairy. Moderate: wine, alcohol
Tussing-Humphreys, 2022^122^ | Control Group | No dietary recommendation provided. No change in MedDiet score from baseline to follow-up, lower score than MedDiet & MedDiet+ER at follow-up
Roussell, 2014 ^129^ | Healthy American Diet (HAD) | Fruits and juices (3.1 cups); Vegetables (3.2 cups); Grains (8.3 oz); low-fat dairy (1.2 cups); high-fat dairy (0.7 cups); legumes, nuts, seeds and other vegetables (0.6 oz); beef (0.7 oz); poultry, pork, fish (3.7 oz); egg and egg-product substitutes (0.24 oz); fats and oils (5.4 g)
Roussell, 2014 ^129^ | DASH | Fruits and juices (4.1 cups); Vegetables (4.3 cups); Grains (4.5 oz); low-fat dairy (2.3 cups); high-fat dairy (0.1 cups); legumes, nuts, seeds and other vegetables (2.1 oz); beef (1.0 oz); poultry, pork, fish (3.7 oz); egg and egg-product substitutes (0.2 oz); fats and oils (4.0 g)
Roussell, 2014 ^129^ | Beef in an Optimal Lean Diet (BOLD): | Fruits and juices (4.5 cups); Vegetables (3.9 cups); Grains (5.6 oz); low-fat dairy (1.8 cups); high-fat dairy (0.0 cups); legumes, nuts, seeds and other vegetables (1.3 oz); beef (4.0 oz); poultry, pork, fish (1.0 oz); egg and egg-product substitutes (0.1 oz); fats and oils (4.3 g)
Roussell, 2014 ^129^ | BOLD plus additional protein (BOLD+): | Fruits and juices (3.4 cups); Vegetables (4.6 cups); Grains (5.3 oz); low-fat dairy (4.7 cups); high-fat dairy (0.0 cups); legumes, nuts, seeds and other vegetables (4.2 oz); beef (5.4 oz); poultry, pork, fish (1.0 oz); egg and egg-product substitutes (0.9 oz); fats and oils (1.4 g)

#### Outcomes

Studies in this body of evidence assessed three broad group of outcomes:

- CVD-related mortality: Forty-six articles (all PCS) assessed CVD-related mortality.^22,23,25,32,37,38,42,44–46,51–53,55,57–60,65,67,70,73,77–80,83,84,88,89,91,93–95,97,99,100,102,105,106,109,111–114^ While most studies reported CVD-related mortality at a broad level, some studies provided additional specifications (e.g. stroke mortality, CVD mortality, sudden cardiac death, heart disease death). CVD-related mortality was generally identified using National Death Index, sometimes in conjunction with state registries. Some studies also used medical records, ICD codes and adjudication to classify the cause of death.
- CVD-related morbidity: Two articles from one trial^119,123^ and 49 PCS articles assessed CVD-related morbidity.^20,21,24,27–31,33–36,39–41,43,44,47–50,52,54,55,58,62–64,66,71–75,82,86,87,90,92,96,101,103,104,108,110,115,119,123,125^ The common outcomes considered under the broad umbrella of CVD-related morbidity included: Heart failure, CVD, coronary heart disease, stroke, peripheral artery disease, and coronary artery calcification. A few studies also presented a composite of CVD-morbidity and mortality. Most of the CVD-morbidity related outcomes were assessed using medical record abstraction, sometimes along with adjudication, and CT scanners. In case of composite CVD-morbidity and mortality, studies commonly assessed fatal outcomes using National Death Index and/or death certificates. Five articles relied primarily on self-report for outcome assessment.^31,35,36,90,108^ Except one article, some or all of the outcomes were adjudicated. A few studies combined “confirmed” outcomes along with “probable” outcomes which were not confirmed using medical records.^24,44,86,96^ Outcome ascertainment was not very clearly described in three articles.^71,72,82^
- Intermediate outcomes: Eight articles (from 7 trials) and 18 articles (PCS) assessed intermediate outcomes such as hypertension,^21,36,61,76,107,124,126–128^ blood pressure (systolic and diastolic),^21,37,69,85,98,107,116–118,120–123,128,129^ cholesterol (HDL-C, LDL-C) and triglycerides.^21,26,34,36,56,69,76,81,85,98,116,118,120–122^ The majority of the studies measured lipid panel after 8-12 hours of fasting, although this was unclear in a RCT^120^ and a prospective cohort study.^56^ Blood pressure was generally assessed using multiple measurements, except one trial that assessed blood pressure only once.^129^

### Synthesis of the evidence

This body of evidence included studies that were conducted only in the U.S. in order to focus the update on studies that are most applicable to the U.S. population in terms of dietary intake, risk of cardiovascular disease, and other factors that may impact the relationship being examined. During the synthesis, health equity was considered in order to understand whether the findings were applicable across participants from diverse racial or ethnic groups or of varied socioeconomic positions. After reviewing the results across all included articles, the results from a sub-set of the articles that included a majority of non-White participants were separately considered. It was determined that findings reported in this sub-set of articles were consistent with the overall body of evidence, especially for race and/or ethnicity. Findings were generally consistent across different socioeconomic positions, although this data was not available for all the studies. The synthesis of the evidence, below, considers the full body of evidence, and also acknowledges results from studies conducted with participants of diverse racial or ethnic groups or of varied socioeconomic positions.

#### Dietary patterns associated with lower risk of CVD

Seventy-three articles (including 6 RCT^116–118,120,123,129^ and 67 PCS^20–24,30,31,33–36,38,40,42–45,47,48,50–52,54,56,58,61–65,67,68,70,71,73,74,77,78,80,82–85,90,91,94–99,101,102,104,106,109–113,115,124,126,127^ (Table 11 and Table 12)) reported that lower risk of CVD was associated with greater alignment to dietary patterns emphasizing vegetables, fruits, legumes, nuts, whole grains with lower intakes of red and processed meat, sugar-sweetened foods and beverages. These patterns also emphasized sources of unsaturated relative to saturated fats (e.g., olive oil, MUFA+PUFA/SFA ratio), as well as less sodium. Some of the dietary patterns associated with lower risk of CVD did not include animal-based components, such as diets described as “plant-based”. The dietary patterns related to lower risk of CVD that did include animal-based components tended to reflect: higher intakes of low-fat dairy and seafood (including fish).

Table 11 Randomized controlled trial studies examining the relationship between dietary patterns consumed in adults and older adults and risk of CVD^a^

Article Information | Intervention and comparator | Results | Mehodological considerations
Jeong, 2023^116^; United States; DASH; Analytic N=437; Participant characteristics:; - [underlined: Race and/or Ethnicity]: Black: 49%; - [underlined: SEP]: NR; - [underlined: Selection:] Excluded participants for hyperlipidemia, a CVD event within the previous 6 months, body mass index (BMI) >35 kg/m2, renal insufficiency, excessive alcohol intake (>14 drinks/week), or poorly controlled diabetes mellitus; Participants not taking antihypertensive or diabetes mellitus medications were enrolled. Participants required to have an average SBP <160 mm Hg and an average diastolic BP (DBP) between 80 and 95 mm Hg; 45% to 52% were women; - BMI >30: 35%; Mean BMI: ~28 kg/m2; - Hypertension: 26% | - DP Age(s): 22 to 75 y at baseline; Mean age: 45 y; - DP(s) examined: DASH; - DP Components: DASH: Positive: Fruits and vegetables (9.6 servings), fat-free or low fat dairy, whole grains, poultry, fish, nuts, seeds and legumes; Negative: Saturated and total fat, cholesterol, sweets and sugary beverages. Magnesium, Potassium and Calcium at 75th percentile of US consumption; - F/V diet: Fruits and vegetables (8.5 servings), nuts, seeds and legumes; High in red meats. High in total fat, saturated fat and cholesterol. High in fiber. Potassium, Magnesium at 75% US consumption; - Control: Fruits and vegetables (3.6 servings), red meats, snacks, and sweets. High in total fat, saturated fat and cholesterol. Low in fiber. K, Mg, and Ca at 25th of US consumption.; - DP Method(s): Other RCT; Comparisons: DASH vs. F/V, Control | Follow-Up Duration: 8 wks; Absolute difference in SBP, mm Hg; Control: −1.3 (−2.5, −0.2); p-value: <0.05; F/V: −3.8 (−5.0, −2.7); p-value: <0.05; DASH: −6.7 (−7.8, −5.5); p-value: <0.05; F/V vs. Control: −2.5 (−4.2, −0.8); p-value: <0.05; DASH vs. Control: −5.3 (−7.0, −3.7); pvalue: <0.05; DASH vs. F/V: −2.8 (−4.5, −1.2); p-value: <0.05; Absolute difference in HDL Cholesterol, mg/100 ml; Control: 0.3 (−0.7, 1.3); F/V: 0.0 (−1.0, 1.0); DASH: −3.5 (−4.5, −2.5); p-value: <0.05; F/V vs. Control: −0.2 (−1.7, 1.2); DASH vs Control: −3.8 (−5.2, −2.4); p-value: <0.05; DASH vs. F/V: −3.5 (−5.0, −2.1); p-value: <0.05; Summary: SBP: DASH vs. control, DASH vs. F/V significant; HDL-C: DASH vs. control, DASH vs. F/V significant | - Outcome measurement: Biomarkers measured after 12 hr fasting; - Trial conducted more than 30 years ago and American diet could have changed since. It is unclear which foods and food groups were included as part of each pattern as DP mentioned in the supplement is not congruent with the manuscript. Participants were not blinded. Details of randomization is not clearly documented.; - Funding: NHLBI
Juraschek, 2017^117^; United States; DASH; Analytic N=412; Participant characteristics:; - [underlined: Race and/or Ethnicity]:; Black: 57%; White: 40%; Asian/Other: 3-5%; - [underlined: SEP]: College graduate or attended college: >80%; - Annual income <$30,000: 32-34%; - [underlined: Selection:] Excluded participants with a prior diagnosis of heart disease, renal insufficiency, poorly controlled dyslipidemia, diabetes mellitus, or heart failure. All participants had prehypertension or stage I hypertension. Also excluded were those using antihypertensive agents, insulin, or drinking more than 14 alcoholic drinks a week. 57% women; - Obesity: 39%; Mean BMI: 29.2 kg/m2; - High BP: 41% | - DP Age(s): >22 y at baseline; Mean age: 48.2 y;; - DP(s) examined: DASH; - DP Components: DASH: Positive: Fruits (5.2 servings), vegetables (4.4 servings), low-fat dairy (2.0 servings), regular fat dairy (0.7 servings), whole grains (7.5 servings), poultry (0.6 servings), fish (0.5 servings), nuts, seeds, legumes (0.7 servings); Negative: Red meat (beef, portk , ham - 0.5 servings), snacks and sweets (0.7 servings). SSB, reducted intake of saturated fat, total fat, cholesterol (fats, oils and salad dressings - 2.5 servings); - Control: Typical American diet - Fruits (1.6 servings), vegetables (2.0 servings), Grains (8.2 servings), Low-fat dairy (0.1 serving), Regular-fat dairy (0.4 serving), Nuts, seeds, and legumes (0.0 servings), Beef, pork, and ham (1.5 servings), Poultry (0.8 servings), Fish (0.2 servings), Fat, oils, and salad dressing (5.8 servings), snacks and sweets (4.1 servings); - DP Method(s): Other RCT; Comparisons: DASH vs. Control | Follow-Up Duration: 12 wks; SBP mm Hg, Week 4; DASH: 125.4 (11.5) vs. Control: 129.6 (11.7); Difference: −4.22 (−6.49,−1.95); P-value: 0.0003; SBP, Week 8; DASH: 124.5 (10.5) vs. Control: 130.0 (11.7); Difference: −5.45 (−7.66,−3.24); P-value: <0.001; SBP, Week 12; DASH: 125.3 (11.0) vs. Control: 129.2 (11.2); Difference: −3.82 (−6.03,−1.61); P-value: 0.0008; DBP, mm Hg, Week 4; DASH: 80.7 (6.9) vs. Control: 82.1 (6.7); Difference: −1.43 (−2.76,−0.09); P-value: 0.04; DBP, Week 8; DASH: 79.5 ( 6.8) vs. Control: 81.8 (6.4); Difference: −2.35 (−3.66,−1.04); P-value: 0.001; DBP, Week 12; DASH: 80.0 ( 6.6) vs. Control: 81.0 (6.7); Difference: −0.99 (−2.32, 0.33); P-value: 0.14; [underlined: Participants with hypertension at baseline:]; SBP, Week 4; DASH: 132.2 (12.2) vs. Control: 137.9 (11.7); Difference: −5.69 (−9.39,−1.99); P-value: 0.003; SBP, Week 8; DASH: 130.4 (10.0) vs. Control: 138.2 (12.1); Difference: −7.82 (−11.31,−4.32); P-value: <0.001; SBP, Week 12; DASH: 131.9 (10.8) vs. Control: 136.0 (11.5); Difference: −4.06 (−7.60,−0.52); P-value: 0.02; DBP, Week 4; DASH: 83.7 ( 6.9) vs. Control: 84.9 ( 6.7); Difference: −1.23 (−3.34, 0.87); P-value: 0.25; DBP, Week 8; DASH: 82.1 ( 6.2) vs. Control: 84.3 ( 6.7); Difference: −2.22 (−4.26,−0.17); P-value: 0.03; DBP, Week 12; DASH: 82.9 ( 6.6) vs. Control: 83.0 ( 6.5); Difference: −0.06 (−2.15, 2.03); P-value: 0.95; Summary: Inverse: DASH vs. control for SBP (all participants & only with hypertension at baseline); Inverse: DASH vs. control sig for DBP in all participants (at wks 4, 8); Null: DASH vs. control for DBP for all participants (at 12 weeks) and only with hypertension | - Outcome measurement: BP measured multiple times; - Within each group, participants were on low, intermediate and high sodium intake. While this can be a co-intervention, it is probably not differential. Participants were not blinded. Details of randomization is not clearly documented.; - Funding: NHLBI, NCRR
Krishnan, 2018^118^; United States; NR; Analytic N=44, 22/group; Participant characteristics:; - [underlined: Race and/or Ethnicity]: NR; - [underlined: SEP]: NR; - [underlined: Selection:] Excluded participants if resting blood pressure >140/90 mm Hg, Hb <11.5 g/dL, total cholesterol >300 mg/dL, LDL cholesterol >189 mg/dL, TG >400 mg/dL, or clinically abnormal thyroid or liver function. Other exclusion: presence of any metabolic diseases, GI disorders, cancer or other serious chronic disease; pregnancy or lactation; current use of tobacco; prescribed or OTC weightloss medications in the 6 mo before enrollment into the study; moderate or strenuous physical activity >30 min/d on ≥5 d/wk; weight change of >5% of body weight within 6 mo of entry into the study; “graveyard” work shifts or forced to stay awake all night; dietary restrictions that would interfere with consuming the intervention foods; or use of medications for elevated lipids or glucose; - BMI at baseline: 25.2 to 39.8; - Pre- and postmenopausal women who were overweight or obese, who did not meet the minimal physical activity guidelines of 150 min/wk and had ≥1 cardiometabolic risk factor were included. Resting BP: ≤140/90 mm Hg. Several indexes of glucose intolerance and insulin resistance were considered as inclusion criteria on the basis of American Diabetes Association guidelines. Alternatively, volunteers could qualify based of ATP III guidelines criteria: fasting triglyceride concentrations >150 mg/dL or HDL cholesterol <50 mg/dL. | - DP Age(s): 20 to 65 y; Typical American Diet (TAD) group: Mean age: ~47 y; Dietary Guidelines for Americans group: Mean age: ~47 y; - DP(s) examined:; - Dietary Guidelines for Americans, based on the food-group recommendations set forth by the 2010 Dietary Guidelines for Americans; - TAD, based on based on dietary intake reported by participants in the USDA’s “What We Eat in America” survey; - DP Components:; - Dietary Guidelines for Americans: Fruits (total): 2.3 cups (whole fruit 1.6 c, juice: 0.7 c); Vegetables (total): 3.4 cups (Dark green: 0.4, red and orange: 1.1, beans and peas: 0.3, starchy vegetables: 0.8, other vegetables: 0.9); Grains: 5.2 ounces (whole grain: 2.8; enriched refined grains: 2.4); Meat, fish, poultry, eggs, nuts and seeds ounces: 5.2 ounces (seafood: 1.1; Meat, poultry, eggs: 3.4; Nuts, seeds, soy products: 0.8); Dairy: 3.3 c; Oils, g: 33.1; Solid fats and added sugars, kcal: 333 (% of energy: 15); - TAD: Fruits (total): 1 cups (whole fruit 0.4 c, juice: 0.6 c); Vegetables (total): 1.5 cups (Dark green: 0.12 c, red and orange: 0.3 c, beans and peas: 0.1 c, starchy vegetables: 0.54 c, other vegetables: 0.5 c); Grains: 6.8 ounces (whole grain: 1.1; enriched refined grains: 5.7); Meat, fish, poultry, eggs, nuts and seeds ounces: 6.5 ounces (seafood: 0.6; Meat, poultry, eggs: 5.4; Nuts, seeds, soy products: 0.5); Dairy: 1.5 c; Oils, g: 22.4; Solid fats and added sugars, kcal: 757 (% of energy: 33); - DP Method(s): Other RCT; Comparisons: DGA & TAD (within- and between- group differences) | Follow-Up Duration: 8 wks; Fasting LDL Cholesterol, mg/dL:; TAD:; Week 1: 127.2 ± 22.4; Week 2: 133.7 ± 22.9; Week 8: 130.2 ± 22.3; Dietary Guidelines for Americans; Week 1: 123.3 ± 28.1; Week 2: 122.0 ± 28.3; Week 8: 117.4 ± 21.2; Fasting HDL Cholesterol, mg/dL:; TAD; Week 1: 45.6 ± 9.4; ITT; Week 2: 44.1 ± 10.3; Week 8: 41.5 ± 10.3; Main effect of group and week (P=0.001) and no interaction effect; Wk 0 vs. Wk 2: P=0.004; Week 0 vs. week 8: P<0.001; Week 2 vs. week 8: P=0.053; Dietary Guidelines for Americans; Week 1: 50.4 ± 11.1; Week 2: 48.0 ± 8.0; Week 8: 47.0 ± 9.5; Main effect of group and week (P=0.001) and no interaction effect; Wk 0 vs. Wk 2: P=0.004; Week 0 vs. week 8: P<0.001; Week 2 vs. week 8: P=0.053 Fasting TG:; TAD; Week 1: 112.5 ± 58.7; Week 2: 129.4 ± 66.7; Week 8: 130.4 ± 77.8; Dietary Guidelines for Americans; Week 1: 141.1 ± 101.3; Week 2: 130.0 ± 78.8; Week 8: 142.6 ± 93.1; SBP, mm Hg:; TAD; Week 1: 119.7 ± 10.2; Week 2: 119.7 ± 8.4; Week 8: 117.3 ± 8.3; Dietary Guidelines for Americans; Week 1: 125.1 ± 14.9; Week 2: 121.5 ± 9.8; Week 8: 118.8 ± 9.1; Main effect of group (P=0.044) and week (P=0.017) and a trend for interaction (P = 0.09). Dietary Guidelines for Americans Wk 1 vs significantly different than Dietary Guidelines for Americans Wk 8 (P=0.006); DBP, mm Hg; TAD; Week 1: 72.8 ± 6.9; Week 2: 70.9 ± 4.4; Week 8: 70.3 ± 6.3; Dietary Guidelines for Americans; Week 1: 72.0 ± 8.5; Week 2: 71.7 ± 7.4; Week 8: 71.0 ± 7.4; Per-protocol, TAD (n=22), Dietary Guidelines for Americans (n=22); Fasting LDL-C, mg/dL; TAD; Week 0: 130.5 ± 20.2; Week 2: 135.6 ± 21.9; Week 8: 128.9 ± 23.0; Dietary Guidelines for Americans; Week 0: 122.0 ± 30.2; Week 2: 120.2 ± 28.1; Week 8: 118.7 ± 21.3; Fasting HDL-C, mg/dL; TAD; Week 0: 47.1 ± 10.0; Week 2: 45.6 ± 10.4; Week 8: 44.0 ± 9.0; Week 0 vs. Week 8, P <0.001; Dietary Guidelines for Americans; Week 0: 51.4 ± 11.6; Week 2: 46.6 ± 8.3; Week 8: 44.4 ± 11.1; Week 0 vs. Week 8, P <0.001; Main week (P<0.001) and group (<0.001) effects; Fasting TG, mg/dL; TAD; Week 0: 118.7 ± 58.1; Week 2: 129.4 ± 66.7; Week 8: 126.7 ± 80.1; Dietary Guidelines for Americans; Week 0: 143.1 ± 100.7; Week 2: 130.0 ± 78.8; Week 8: 142.6 ± 93.1; SBP, mmHg; TAD; Week 0: 118.9 ± 10.3; Week 2: 120.5 ± 8.4; Week 8: 117.5 ± 8.0; Dietary Guidelines for Americans; Week 0: 127.9 ± 14.7; Week 2: 120.8 ± 9.9; Week 8: 118.6 ± 9.3; Lower SBP at weeks 2 (P=0.05) and 8 (P=0.001) vs. week 0; Significant week effect (P=0.002), group*week interaction (P=0.04); Fasting DBP, mmHg; TAD; Week 0: 72.7 ± 6.8; Week 2: 71.0 ± 4.5; Week 8: 70.8 ± 6.5; Dietary Guidelines for Americans; Week 0: 72.9 ± 6.8; Week 2: 71.5 ± 7.4; Week 8: 70.5 ± 7.2; Summary: Dietary Guidelines for Americans vs. TAD: Sig within group difference in HDL cholesterol (Weeks 0 vs. 2 vs. 8); Within Dietary Guidelines for Americans: Sig within group difference in SBP (weeks 0 vs. 8); NS/Null: No difference within or between Dietary Guidelines for Americans & TAD in LDL-C, TG, DBP | - Did not account for: RCT; - Outcome measurement: Fasting lipid panel; - Shorter duration, smaller sample size; TAD had more physical activity (not significantly different than Dietary Guidelines for Americans); Self-report and visual inspection of returned food and packaging are imperfect tools for measuring adherence. No report on race and/or ethnicity or SEP. It is unclear if the participants that were randomized and refused to participate are any different than those that continued.; - Funding: National Dairy Council, Campbell Soup Co, USDA ARS
Prentice, 2019^119^; United States; WHI Dietary Modification (DM); Analytic N=48,835; Participant characteristics:; - [underlined: Race and/or Ethnicity]:; 81.4% White; 10.8% Black; 3.7% Hispanic; 0.4% American Indian; 2.3% Asian/Pacific Islander; 1.3 % Unknown; - [underlined: SEP]:; High school diploma or GED: ~78%; Family income, ≥50,000: ~39.0%; - [underlined: Selection:] Excluded participants with a prior history of breast or colorectal cancer; Participants with dietary fat intake estimated using an FFQ to be ≥32% of total energy intake were recruited.; - Mean BMI: 28.2 kg/m2; - Former & current smoking: 47.8%; - Hypertension: 43%; - High cholesterol requiring medication: ~12% | - DP Age(s): 50 to 79 y; Mean age at screening: 62.3 y; - DP(s) examined: N/A; - DP Components: Intervention: Reduction in fat from ~35% of energy at baseline to 20% energy+ increase in veg, fruits, grains; vegetables (2.6 cups), fruits (2.5 cups) and total grains (5.4 cups) - whole grain: 1.4 cups; other grains 4.0 cups; - Comparator: Written health-related materials; Veg (2.1 cups); fruits (1.8 cups); total grain (4.7 cups) - wholegrain: 1.1 cups; other grain: 3.6 cups; - DP Method(s): Other RCT; Comparisons: Intervention vs. Comparator | Follow-Up Duration: 8.5 y; Intervention phase, HR, 95% CI; CHD: 0.97, 95% CI: 0.88, 1.08; P-value: 0.61 Stroke: 1.05, 95% CI: 0.92, 1.18; P-value: 0.48; Total CVD: 0.99, 95% CI: 0.92, 1.06; P-value: 0.68; Normotensive, HR, 95% CI; CHD: 0.70, 95% CI: 0.56, 0.87; Stroke: 1.27, 95% CI: 0.99, 1.65; Total CVD: 0.89, 95% CI: 0.77, 1.02; Hypertensive, HR, 95% CI; CHD: 1.04, 95% CI: 0.90, 1.19; Stroke: 0.93, 95% CI: 0.80, 1.10; Total CVD: 0.98, 95% CI: 0.90, 1.08; Cumulative F/U, HR, 95% CI; CHD: 1.02, 95% CI: 0.94, 1.11; P-value: 0.60 Stroke: 1.00, 95% CI: 0.91, 1.10; P-value: 0.98; Total CVD: 1.00, 95% CI: 0.94, 1.05; P-value: 0.92; Normotensive, HR, 95% CI; CHD: 0.85, 95% CI: 0.72, 1.00; Stroke: 1.12, 95% CI: 0.93, 1.34; Total CVD: 0.97, 95% CI: 0.87, 1.07; Hypertensive, HR, 95% CI; CHD: 1.05, 95% CI: 0.94, 1.18; Stroke: 0.92, 95% CI: 0.81, 1.04; Total CVD: 0.97, 95% CI: 0.90, 1.05; Summary: NS/Null: Intervention and control groups for CHD, stroke and total CVD (intervention or cumulative follow-up phase); NS/Null: Intervention and control group for CHD (only f/u), stroke and total (intervention and f/u) after stratified by hypertension; Inverse: Intervention vs. control group for CHD (only in normotensive) | - Did not account for: RCT; - Outcome measurement: Follow-up, adjudicated CVD outcomes; - Randomization was based on vegetables, fruits and grains and the intake of other sources (e.g. meat, dairy) is unclear. Participants were unblinded. Majority of the participants are NHW, so generalizability may be an issue; - Funding: NHLBI
Sidahmed, 2014^121^; United States; Healthy Eating for Colon Cancer Prevention Study; Analytic N=120; Participant characteristics:; - [underlined: Race and/or Ethnicity]: 88% Caucasians; - [underlined: SEP]: NR; - [underlined: Selection:] Excluded those on a medically prescribed diet/require diet counselling, or on a Mediterranean or low-fat diet already; - Enrolled those with one 1st- or 2, 2nd-degree relatives with CRC/polyps; generally healthy; BMI between 18.5 and 35;; - Mean BMI: 27.4 kg/m2 | - DP Age(s): ≥21y at baseline; Mean age: ~53 y; - DP(s) examined: n/a; - DP Components: Healthy eating’ arm: Fruit 2 serv/d, Vegetables 2 serv/d, Dark green or orange vegetables 1 serv/d, Whole grains ≥3 serv/d, SFA <10% Total E; - ‘Mediterranean’ arm: Fruit (vit. C) 1 serv/d, Fruit (Other) 1 serv/d, Allium vegetables 1-2 serv/d, Dark green vegetables 1-2 serv/d, Orange and yellow vegetables 1-2 serv/d, Red vegetables 1-2 serv/d, Other vegetables 1-2 serv/d, Dark green herbs 1 serv/d, Whole grains ≥3 serv/d, High MUFA foods 7-10 exchanges/d, High n-3 foods 3 oz, twice/wk; - DP Method(s): Other RCT; Comparisons: Healthy eating’ arm v. ‘Mediterranean’ arm | Follow-Up Duration: 6 mo; BP; HDL-C; LDL-C - data NR between arms, NS; Summary: NS/Null: ‘Healthy eating’ v. ‘Mediterranean’ and BP, HDL-C, LDL-C | - Did not account for: RCT; - Outcome measurement: Fasting lipid panel; - Low/differential compliance with assigned interventions at 6mo; - Funding: NIH; Cancer Center Support
Tussing-Humphreys, 2022^122^; United States; Building Research in Diet and Cognition study; Analytic N=100; Participant characteristics:; - [underlined: Race and/or Ethnicity]: Predominantly NHB participants (>90%); - [underlined: SEP]: 98.9% have insurance; Median income ~50,000; - [underlined: Selection:] Excluded those with inability to exercise; HbA1c >9%; with autoimmune Dz; severe pulmonary, CV, hepatic, or renal Dz; Warfarin use; severe neurological or psychiatric condition; bariatric sugery; concurrent enrollment in formal weight loss program; participation in cognitive research in 12 months prior; - All participants with BMI: 30-50 kg/m2; Montreal Cognitive Assessment score ≥19; MedDiet score indicating <50% adherence; English-speaking.; - High blood pressure: 62.7%; - High cholesterol: 37.3% | - DP Age(s): 55 to 85 y at baseline; Mean age: ~ 66 y; - DP(s) examined: MedDiet Score [Tangney 2011]; - DP Components: MedDiet Score: Positive: Non-refined grains, potatoes, fruit, vegetables, legumes and nuts, fish, olive oil. Negative: Red and processed meat, poultry, full-fat dairy. Moderate: wine, alcohol; - MedDiet Group: Instruction to follow MedDiet Score recommendations. Increased MedDiet score from baseline to follow-up, higher score than Control Group at follow-up.; - Control Group: No dietary recommendation provided. No change in MedDiet score from baseline to follow-up, lower score than MedDiet & MedDiet+ER at follow-up; - DP Method(s): Index, RCT; Comparisons: Categorical, MedDiet vs. Control | Follow-Up Duration: 8 mo; ∆SBP, mm Hg; MedDiet, mean: 3.2, 95% CI: −1.5, 7.9; Control, mean: 2.6, 95% CI: −3.7, 8.8; group*time interaction, p-trend (all 3 groups)=0.88; MedDiet vs. Control=p>0.05; ∆DBP, mmHg; MedDiet, mean: −0.6, 95% CI: −3.5, 2.3; Control, mean: 1.4, 95% CI: −2.6, 5.3; group*time interaction, p-trend (all 3 groups)=0.73; MedDiet vs. Control=p>0.05; ∆HDL-C, mg/dL; MedDiet, mean: 0.4, 95% CI: −1.8, 2.6; Control, mean: 3.9, 95% CI: 1.0, 6.9; group*time interaction, p-trend (all 3 groups)=0.11; MedDiet vs. Control=p>0.05; ∆LDL-C, mg/dL; MedDiet, mean: 1.5, 95% CI: −5.6, 8.5 ; Control, mean: 2.8, 95% CI: −6.6, 12.1; group*time interaction, p-trend (all 3 groups)=0.51; MedDiet vs. Control=p>0.05; ∆TG, mg/dL; MedDiet, mean: −3.5, 95% CI: −9.6, 2.5; Control, mean: −1.7, 95% CI: −9.8, 6.4; group*time interaction, p-trend (all 3 groups)=0.91; MedDiet vs. Control=p>0.05; Summary: NS/Null: Diet Group & ∆SBP, ∆DBP, ∆LDL-C, ∆HDL-C, ∆TG | - Did not account for: RCT: Smoking, Alcohol, physical activity; - Outcome measurement: Fasting lipid panel; Duplicate BP measurement; - Less adherent participants with a MedDiet score of ≤ 6 out of 13 were excluded; - Funding: NIH
Van Horn, 2021^123^; United States; WHI DMT; Analytic N=10,371; Participant characteristics:; - [underlined: Race and/or Ethnicity]:; ~84% White; ~7% Black; ~3% Hispanic; ~2% Asian/Pacific Islander; ~1.5% Unknown; 0.3% American; Indian/Alaskan Native; - [underlined: SEP]: NR in this article, but based on Prentice et al. from the same trial,; - High school diploma or GED: ~78%; Family income, ≥50,000: ~39.0%; - [underlined: Selection:] Excluded participants with a prior history of CVD, that consumed <36.6% energy from fat, those with implausible energy intake.; - Only normotensive women were included. | - DP Age(s): 50 to 79 y at baseline; Mean age: ~61y; - DP(s) examined: Other RCT; - DP Components: Intervention: Reduce total fat to 20% of total energy intake; increase vegetable and fruit intake to ≥5 servings/d; and increase grain intake to ≥6 servings/d; - Comparator: Printed health-related materials; - DP Method(s): Other RCT; Comparisons: Intervention vs. Comparator | Follow-Up Duration: 1 y; CHD in intervention vs. comparator, HR, 95% CI, 0.70, 95% CI: 0.56, 0.87; P-value: 0.001; ∆SBP, mmHg; Intervention: −0.6 ± 12.4; Comparator: 0.5 ± 12.2; P-value: <0.001; ∆DBP, mmHg; Intervention: −1.3 ± 7.8; Comparator: −0.4 ± 7.6; P-value: <0.001; Summary: Inverse: Low CHD risk in intervention vs. comparator; Inverse: ∆SBP, ∆DBP in the intervention greater than comparator | - Randomization was based on vegetables, fruits and grains and the intake of other sources (e.g. meat, dairy) is unclear. Participants were unblinded. Majority of the participants are NHW and all women were normotensive, so generalizability may be an issue; - Funding: NHLBI/NIH
Schroeder, 2015^120^; United States; NR; Analytic N=27 to 29 per arm; Participant characteristics:; - [underlined: Race and/or Ethnicity]:55.3% NHW, 37.9% NHB, 3.4% Hispanic, 3.4% American Indians; - [underlined: SEP]: NR; - [underlined: Selection:] Excluded participants with regular use of dietary supplements, pre- or probiotics, laxatives, fiber supplements, or antibiotics in the past 3 months. Also participants with condition requiring ongoing medical care or medication (including kidney, liver GI or endocrine disorders) were excluded. Participants with regular tobacco use within 6 mo before study start, history of eating disorders or other atypical DP, weight loss of 10% body weight in the last 12 mo, selfreported alcohol or substance abuse or blood donation 8 weeks prior to the study were excluded. Asian-Americans were excluded.; - Participants with BMI ≥25, serum LDL-C ≥120 mg/dL, but not on cholesterol lowering medications and no aversion to Korean foods were included | - DP Age(s): 25 to 73 y; Mean age: 55.3 y; - DP(s) examined: Korean diet; Dietary Guidelines for Americans diet; Typical American diet (TAD); - DP Components: Korean Diet: Grains (mix of whole and refined); meat, fish, eggs, and beans; vegetables; fruits; and milk and dairy products; Kimchi, fermented bean paste; - Dietary Guidelines for Americans diet (2010/2015): Positive: Vegetables, fruit, whole grains, fiber, seafood, lean meat, legumes and nuts, and low-fat dairy; Negative: sodium, saturated fat, refined grains; - TAD: Positive: High in sodium, saturated fat, refined grains; Negative: Low in vegetables, fruit, whole grains, fiber, lean meats, and dairy; - DP Method(s): Dietary Guidelines for Americans RCT; Comparisons: Korean diet vs. Dietary Guidelines for Americans diet vs. Typical American diet | Follow-Up Duration: 4 weeks; LDL-C (mg/dL); Korean diet: 139.7±25.4; Dietary Guidelines for Americans diet: 142.3±22.4; TAD: 148.3±21.0; P values for differences between diets: <0.01; Korean vs. TAD: <0.01; Dietary Guidelines for Americans vs. TAD: <0.05; Korean vs. Dietary Guidelines for Americans: P>0.05; HDL-C, mg/dL; Korean diet: 48.9±10.7; Dietary Guidelines for Americans diet: 50.0±13.3; TAD: 53.0±13.1; P values for differences between diets: <0.0001; Korean vs. Dietary Guidelines for Americans: P<0.05; Dietary Guidelines for Americans vs. TAD: P<0.05; Korean vs. TAD: P<0.05; TG, mg/dL; Korean diet: 128.0±45.2; Dietary Guidelines for Americans diet: 113.1±49.5; TAD: 118.3±52.2; P values for differences between diets: <0.01; Korean vs. Dietary Guidelines for Americans diet: P<0.05 Korean vs. TAD: P>0.05 Dietary Guidelines for Americans vs. TAD: P>0.05; SBP, mmHg; Korean diet: 117.2±10.5; Dietary Guidelines for Americans diet: 115.3±8.5; TAD: 117.0±10.4; P values for differences between diets: P>0.05; DBP, mmHg; Korean diet: 71.4±7.7; Dietary Guidelines for Americans diet: 69.7±6.8; TAD: 71.8±7.6; P values for differences between diets: P<0.05 Dietary Guidelines for Americans vs. TAD: P<0.05; Korean vs. Dietary Guidelines for Americans: P>0.05; Korean vs. TAD: P>0.05; Summary: Lower LDL-C in Korean and Dietary Guidelines for Americans diet groups vs Typical American diets; Lower HDL-C in Korean vs. Dietary Guidelines for Americans diet and Typical American diet.; Lower HDL-C in Dietary Guidelines for Americans vs. Typical American diet.; Lower TG in Dietary Guidelines for Americans vs. Korean diet group.; Lower DBP in the Dietary Guidelines for Americans diet group vs Typical American diet; Null: SBP across three diet groups | - Outcome measurement: Unclear if biomarker is a fasting measurement; - All participants had mild to moderatly higher LDLC and BMI>25. So, the findings may not be generalizable. Asian Americans were excluded from the study, which may limit the generalizability. The study did not completely blind the participants. Unclear if biomarker is a fasting measurement; - Funding: National Academy of Agricultural Science, Rural Development Administration, Republic of Korea; ARS/USDA
Roussell, 2014^129^; United States; BOLD; Analytic N=36; Participant characteristics:; - [underlined: Race and/or Ethnicity]: NR; - [underlined: SEP]: NR; - [underlined: Selection:] Excluded smokers or participants with established CVD, stroke, hypertension, diabetes, liver, kidney or autoimmune disease, the use of cholesterol/lipid-lowering medication or supplement, being pregnant or lactating, experiencing weight loss of ⩾10% of body weight within the 6 months before enrolling in the study and vegetarianism | - DP Age(s): 39 to 97 y; Mean age: 49 y (males); 50 y (female); - DP(s) examined: Healthy American Diet; DASH; Beef in an Optimal Lean Diet (BOLD); BOLD plus additional protein; - DP Components: Healthy American Diet (HAD): Fruits and juices (3.1 cups); Vegetables (3.2 cups); Grains (8.3 oz); low-fat dairy (1.2 cups); high-fat dairy (0.7 cups); legumes, nuts, seeds and other vegetables (0.6 oz); beef (0.7 oz); poultry, pork, fish (3.7 oz); egg and eggproduct substitutes (0.24 oz); fats and oils (5.4 g); - DASH: Fruits and juices (4.1 cups); Vegetables (4.3 cups); Grains (4.5 oz); low-fat dairy (2.3 cups); high-fat dairy (0.1 cups); legumes, nuts, seeds and other vegetables (2.1 oz); beef (1.0 oz); poultry, pork, fish (3.7 oz); egg and eggproduct substitutes (0.2 oz); fats and oils (4.0 g); - Beef in an Optimal Lean Diet (BOLD): Fruits and juices (4.5 cups); Vegetables (3.9 cups); Grains (5.6 oz); low-fat dairy (1.8 cups); high-fat dairy (0.0 cups); legumes, nuts, seeds and other vegetables (1.3 oz); beef (4.0 oz); poultry, pork, fish (1.0 oz); egg and eggproduct substitutes (0.1 oz); fats and oils (4.3 g); - BOLD plus additional protein (BOLD+): Fruits and juices (3.4 cups); Vegetables (4.6 cups); Grains (5.3 oz); low-fat dairy (4.7 cups); high-fat dairy (0.0 cups); legumes, nuts, seeds and other vegetables (4.2 oz); beef (5.4 oz); poultry, pork, fish (1.0 oz); egg and eggproduct substitutes (0.9 oz); fats and oils (1.4 g); - DP Method(s): Other RCT; - Comparisons: HAD vs. DASH vs. BOLD vs. BOLD+ | Follow-Up Duration: 5 weeks; SBP, mm Hg; HAD: 115.7[underlined: +]1.9; DASH: 112.9[underlined: +]1.9; BOLD: 114.0[underlined: +]1.9; BOLD+: 111.4[underlined: +]1.9; BOLD+ vs. HAD: P<0.05; BOLD+ vs. DASH: P<0.05; BOLD+ vs. BOLD: P<0.05; HAD vs. DASH vs. BOLD: P>0.05; DBP, mm Hg; HAD: 69.8[underlined: +]1.5; DASH: 69.1[underlined: +]1.5; BOLD: 69.4[underlined: +]1.5; BOLD+: 69.1[underlined: +]1.5; P>0.05; HAD vs. DASH vs. BOLD vs. BOLD+: P>0.05; Summary: Lower SBP in BOLD+ when compared to HAD, DASH and BOLD.; No difference in SBP between HAD, DASH and BOLD.; No difference in SBP between HAD, DASH, BOLD and BOLD+ | - Outcome measurement: Single outcome measurement..; - Calorie levels were adjusted based on energy requirements, but nutrients such as sodium, Mg, K and fibre were not increased or decreased proportionally; - Funding: Beef Checkoff Program

a Abbreviations:

DM, Diabetes mellitus (T1D a/o T2D); F/U, Follow-up; HDL,High-density Lipoprotein Cholesterol; HS, high school; HTN, hypertension; Hx, History; ITT, intent-to-treat;LDL,Low-density Lipoprotein Cholesterol; N/A, Not applicable; NR, not reported; NS, not statistically significant Ob, Obesity; OW, Overweight; PA, Physical activity; PP, per-protocol SEP/SES, Socioeconomic position/status; T2D, Type 2 Diabetes; TC, total cholesterol; TG, triglyceride; Tx, Treatment; UPF, Ultra-processed food

Table 12 Observational studies examining the relationship between dietary patterns consumed in adults and older adults and risk of CVD^a^

Article Information | Intervention/exposure and comparator | Results | Methodological considerations
Agha, 2014^20^; United States; WHI; Observational Study; Analytic N=84,537; Participant characteristics:; - [underlined: Race and/or Ethnicity]: 85% NHW; 7% African Americans; 3% Hispanic; - [underlined: SEP]: <10% less than high school; - [underlined: Selection:] Excluded participants with a history of HF at baseline, missing information on of A lifestyle factors, implausible energy intake, underweight due to preclinical disease.; - Hypertension: ~33%; - Mean BMI: ~27 kg/m2 | - DP Age(s): 50 to 79 y at baseline; Mean age: 63.5 y; - DP(s) examined: Alternative HEI (AHEI)-2010 [Chiuve 2012]; - DP Components: AHEI- 2010, Positive: Vegetables; Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol; - DP Method(s): Index; Comparisons: Categorical: Quintile HEI | Follow-Up Duration: 11 y; AHEI vs. HF, HR, 95% CI; Q1: REF; Q2: 0.85, 95% CI: 0.74, 0.97; Q3: 0.81, 95% CI: 0.70, 0.93; Q4: 0.76, 95% CI: 0.65, 0.88; Q5: 0.61, 95% CI: 0.52, 0.73; P-trend: 0.001; Summary: Inverse: AHEI & heart failure | - Did not account for: Total energy intake; - Dietary assessment: Single time point measurement of exposure; - Outcome measurement: HF is based on self-reported hospitalization and medical records, which could be more severe and have missed some cases; - HF is based on self-reported hospitalization and medical records, which could be more severe and have missed some cases. Single dietary intake assessment.; - Funding: NHLBI
Ahmad, 2018^21^; United States; Women’s Health Study; Analytic N=25,994; Participant characteristics:; - [underlined: Race and/or Ethnicity]: NR; - [underlined: SEP]: 100% Health professionals; - [underlined: Selection:] Excluded participants with missing biomarker data or MED intake; Participants free from CVD at baseline. | - DP Age(s): > 45 y at baseline; Mean age at baseline: 54.7 y; - DP(s) examined: MED score; - DP Components: Med Score: Positive: Vegetables (not potatoes); Legumes; Fruit and Nuts; Whole grains; Fish; MUFA/SFA. Negative: Red and Processed Meat; Dairy Products. Neutral: Alcohol; - DP Method(s): Index; Comparisons: Categorical: Tertile of MED diet score | Follow-Up Duration: 12 y; MED Score vs. CVD, HR, 95% CI; MED score (0-3): REF; 4-5: 0.85, 95% CI: 0.73, 0.98; ≥6: 0.85, 95% CI: 0.71, 1.01; P-trend: 0.04; MED Score vs. CVD, Tertile, HR, 95% CI +BMI; MED score (0-3): REF; 4-5: 0.87, 95% CI: 0.75, 1.01; ≥6: 0.89, 95% CI: 0.75, 1.06 P-trend: 0.14; MED Score vs. Hypertension, HR, 95% CI MED Score (0-3): REF; 4-5: 0.79, 95% CI: 0.69, 0.92; ≥6: 0.75, 95% CI: 0.63, 0.89; P-trend: 0.001; MED Score vs. Systolic BP, HR, 95% CI MED Score (0-3): REF; 4-5: 0.81, 95% CI: 0.70, 0.94; ≥6: 0.77, 95% CI: 0.65, 0.91; P-trend: 0.002; MED Score vs. Diastolic BP, HR, 95% CI MED Score (0-3): REF; 4-5: 0.79, 95% CI: 0.69, 0.92; ≥6: 0.75, 95% CI: 0.63, 0.89; P-trend: <0.001; Med Score vs. LDL, HR, 95% CI MED Score (0-3): REF; 4-5: 0.78, 95% CI: 0.67, 0.90; ≥6: 0.72, 95% CI: 0.61, 0.86; P-trend: <0.001; Med Score vs. HDL-C, HR, 95% CI MED Score (0-3): REF; 4-5: 0.80, 95% CI: 0.70, 0.93; ≥6: 0.78, 95% CI: 0.65, 0.92; P-trend: 0.002; Med Score vs. TG, HR, 95% CI; MED Score (0-3): REF; 4-5: 0.78, 95% CI: 0.68, 0.91; ≥6: 0.75, 95% CI: 0.63, 0.89; P-trend: <0.001; Summary: Inverse: Med score & CVD, hypertension, SBP, DBP, LDL-C, HDL-C, TG; NS/Null: Med score vs. CVD events after adjusting for; BMI | - Did not account for: Race and/or ethnicity, SEP (health professionals); - Dietary assessment: Single time point measurement of exposure; - Outcome measurement: Medical record abstraction; - Single time point measurement of exposure; Part of WHS, where health professionals were randomized to low-dose aspirin or vit E after baseline data collection. Although this study had a long follow-up, it is unclear if the trial had an impact on this study outcome - although it would be non-differential.; - Funding: NIH, Swedish Heart-Lung Foundation, Nutricia Research Foundation, Henning och Johan Throne-Holst stiftelse Fellowship, American Heart Association, Molino Family
Aigner, 2018^22^; United States; Multiethnic Cohort Study; Analytic N=172,043; Participant characteristics:; - [underlined: Race and/or Ethnicity]: 25.8% White; 15.6% African American; 7.4% Native Hawaiian; 29.6% Japanese American 21.6% Latino; - [underlined: SEP]: <12 y of education: ~16%; - [underlined: Selection:] Excluded participants in the “other” ethnic group, invalid dietary assessment information (implausible energy and macronutrient intake) and missing covariates; - Hypertension: 39.9%; - Previous heart attack/angina: 8.0%; - Current or former smoking: 58%; - BMI >25 kg/m2: 62.5% | - DP Age(s): 45 to 75 y at baseline; Mean age: 59.1 y; - DP(s) examined: Healthy Eating Index (HEI-2010) [Guenther 2013]; - Alternative HEI (AHEI)-2010 [Chiuve 2012]; - aMED [Fung, 2005]; - DASH [Fung, 2008]; - DP Components: HEI-2010: Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; Fatty Acids (PUFA+MUFA/SFA). Negative: Refined Grains; Added Sugars in “Empty Calories”; Solid Fats in “Empty Calories”; Sodium; - AHEI-2010: Positive: Vegetables; Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol; - aMED: aMED: Positive: Vegetables; Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA/SFA; Neutral: Red and Processed Meat; Neutral: Alcohol; - DASH: Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Sodium; - DP Method(s): Index; Comparisons: Categorical: Tertile, Medium or Low vs. High | Follow-Up Duration: 17.6 y, mean; HEI-2010 vs. Stroke mortality, HR, 95% CI; High: REF; Medium: 1.06, 95% CI: 0.98, 1.15; Low: 1.23, 95% CI: 1.13, 1.34; AHEI-2010 vs. Stroke mortality, HR, 95% CI; High: REF; Medium: 1.04, 95% CI: 0.96, 1.13; Low: 1.01, 95% CI: 1.01, 1.20; aMED vs. Stroke mortality, HR, 95% CI High: REF; Medium: 1.04, 95% CI: 0.95, 1.14; Low: 1.13, 95% CI: 1.04, 1.24; DASH vs. Stroke mortality, HR, 95% CI; High: REF; Medium: 1.00, 95% CI: 0.92, 1.08; Low: 1.05, 95% CI: 0.96, 1.14; HEI-2010 vs. Stroke mortality, 95% CI; Men; High: REF; Medium: 1.03, 95% CI: 0.91, 1.16; Low: 1.18, 95% CI: 1.05, 1.34; Women; High: REF; Medium: 1.07, 95% CI: 0.94, 1.22; Low: 1.26, 95% CI: 1.09, 1.46; AHEI-2010 vs. Stroke mortality, 95% CI; Men; High: REF; Medium: 0.99, 95% CI: 0.88, 1.11; Low: 1.04, 95% CI: 0.92, 1.17; Women; High: REF; Medium: 1.07, 95% CI: 0.93, 1.22; Low: 1.17, 95% CI: 1.01, 1.36; aMED vs. Stroke mortality, HR, 95% CI; Men; High: REF; Medium: 0.97, 95% CI: 0.85, 1.11; Low: 1.13, 95% CI: 1.00, 1.28; Women; High: REF; Medium: 1.03, 95% CI: 0.88, 1.21; Low: 1.14, 95% CI: 0.99, 1.32; DASH; Men; High: REF; Medium: 1.04, 95% CI: 0.92, 1.16; Low: 1.04, 95% CI: 0.92, 1.18; Women; High: REF; Medium: 0.94, 95% CI: 0.82, 1.08; Low: 1.03, 95% CI: 0.88, 1.19; HEI-2010 vs. Stroke mortality, HR, 95% CI; White; High: REF; Medium: 1.17, 95% CI: 0.95, 1.44; Low: 1.52, 95% CI: 1.22, 1.88; African American; High: REF; Medium: 1.06, 95% CI: 0.87, 1.30; Low: 1.23, 95% CI: 1.00, 1.53; Native Hawaiian; High: REF; Medium: 1.03, 95% CI: 0.70, 1.52; Low: 1.17, 95% CI: 0.78, 1.76; Japanese American; High: REF; Medium: 1.11, 95% CI: 0.94, 1.31; Low: 1.19, 95% CI: 0.99, 1.44; Latino; High: REF; Medium: 0.88, 95% CI: 0.70, 1.09; Low: 0.82, 95% CI: 0.82, 1.27; AHEI-2010 vs. Stroke mortality; White; High: REF; Medium: 1.09, 95% CI: 0.91, 1.29; Low: 1.15, 95% CI: 0.96, 1.38; African American; High: REF; Medium: 1.10, 95% CI: 0.92, 1.32; Low: 1.15, 95% CI: 0.95, 1.39; Native Hawaiian; High: REF; Medium:1.02, 95% CI: 0.74, 1.42; Low: 1.21, 95% CI: 0.85, 1.73; Japanese American; High: REF; Medium: 0.98, 95% CI: 0.85, 1.12; Low: 1.17, 95% CI: 1.00, 1.38; Latino; High: REF; Medium: 1.07, 95% CI: 0.89, 1.30; Low: 1.00, 95% CI: 0.82, 1.21; aMED vs. Stroke mortality White; High: REF; Medium: 0.89, 95% CI: 0.70, 1.14; Low: 1.02, 95% CI: 0.83, 1.26; African American; High: REF; Medium: 0.81, 95% CI: 0.63, 1.05; Low: 1.14, 95% CI: 0.92, 1.41; Native Hawaiian; High: REF; Medium: 1.12, 95% CI: 0.72, 1.73; Low: 1.15, 95% CI: 0.75, 1.76; Japanese American; High: REF; Medium: 0.97, 95% CI: 0.80, 1.19; Low: 1.25, 95% CI: 1.05, 1.50; Latino; High: REF; Medium: 1.29, 95% CI: 1.03, 1.63; Low: 1.07, 95% CI: 0.86, 1.34; DASH vs. Stroke mortality; White; High: REF; Medium: 0.96, 95% CI: 0.78, 1.18; Low: 1.25, 95% CI: 1.00, 1.57; African American; High: REF; Medium: 1.07, 95% CI: 0.86, 1.32; Low: 1.16, 95% CI: 0.93, 1.45; Native Hawaiian; High: REF; Medium: 0.86, 95% CI: 0.58, 1.28; Low: 0.87, 95% CI: 0.57, 1.32; Japanese American; High: REF; Medium: 1.01, 95% CI: 0.85, 1.20; Low: 1.00, 95% CI: 0.83, 1.19; Latino; High: REF; Medium: 0.93, 95% CI: 0.76, 1.14; Low: 0.84, 95% CI: 0.67, 1.06; Summary: Inverse: HEI-2010 (low) & stroke mortality (in both men and women; in White, African American); Inverse: AHEI-2010 (low) & stroke mortality (in women only); Inverse: aMED (low) & stroke mortality (overall only; in Japanese American, Latino (medium aMED); Null: DASH & stroke mortality (overall, men, women); Null: AHEI-2010 & stroke motality in men | - Did not account for: None (all); - Dietary assessment: Single time point measurement of exposure; - Outcome measurement: Stroke subtype data is unreliable; - Single time point measurement of exposure; Stroke subtype data is unreliable; - Funding: NCI
Baden, 2019^23^; United States; NHS, HPFS; Analytic N=75,314; Participant characteristics:; - [underlined: Race and/or Ethnicity]:96-98% White; - [underlined: SEP]: 100% Nurses, Health professionals; - [underlined: Selection:] Excluded participants who died before baseline, had history of CVD, cancer at or before baseline, missing dietary information or had implausible energy intakes | - DP Age(s): 30 to 55 y at baseline, NHS; - 40 to 75 y at baseline, HPFS; - Mean age at baseline: ~62-64; - DP(s) examined: Plant-Based Diet Index (PDI) [Kim 2018]; Healthy Plant-Based Diet Index (hPDI) [Kim 2018]; Unhealthy Plant-Based Diet Index (uPDI) [Kim 2018]; - DP Components: PDI: Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Negative: Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; - hPDI: Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Negative: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; - uPDI: Negative: Whole grains; Fruits; Vegetables; Nuts; Legumes; Vegetable oils; Tea/coffee; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; Positive: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; - DP Method(s): Index; Comparisons: Continuous, Per-10-pt increase, Quintiles of PDI, hPDI and uPDI | Follow-Up Duration: 12 y; DP (per 10-point increase) vs. CVD mortality, HR, 95% CI (Pooled); PDI: 0.93, 95% CI: 0.88, 0.99; hPDI: 0.91, 95% CI: 0.86, 0.96; uPDI: 1.08, 95% CI: 1.02, 1.14; CVD mortality, 10-point increase Nurses’s Health Study; PDI: 0.95, 95% CI: 0.87, 1.03; hPDI: 0.92, 95% CI: 0.85, 0.99; uPDI: 1.10, 95% CI: 1.02, 1.18; Health Professionals Follow-up Study; PDI: 0.91, 95% CI: 0.83, 0.99; hPDI: 0.90, 95% CI: 0.83, 0.98; uPDI: 1.05, 95% CI: 0.97, 1.14; DP (per 10-point increase) vs. CHD mortality Nurse’s Health Study; PDI: 0.93, 95% CI: 0.84, 1.02; hPDI: 0.88, 95% CI: 0.81, 0.97; uPDI: 1.12, 95% CI: 1.03, 1.22; Health Professionals Follow-up Study; PDI: 0.89, 95% CI: 0.81, 0.98; hPDI: 0.87, 95% CI: 0.80, 0.95; uPDI: 1.09, 95% CI: 0.99, 1.19; Stroke mortality; Nurse’s Health Study; PDI: 0.99, 95% CI: 0.86, 1.15; hPDI: 0.99, 95% CI: 0.87, 1.13; uPDI: 1.04, 95% CI: 0.92, 1.18; Health Professionals Follow-up Study; PDI: 1.01, 95% CI: 0.82, 1.23; hPDI: 1.04, 95% CI: 0.86, 1.26; uPDI: 0.90, 95% CI: 0.74, 1.08; Summary: Inverse: Overall PDI, hPDI & CVD mortality; hPDI & CHD mortality; Positive: uPDI & CVD-mortality, CHD mortality; NS/Null: Overall PDI & CHD mortality; Overall PDI, hPDI & uPDI & stroke mortality | - Did not account for: None (all); - Dietary assessment: Multiple exposure assessment; - Outcome measurement: National Death Index, family, medical records + adjudication; - Generalizability may be an issue, since the participants are White and health professionals. Possible overadjustments in models; - Funding: NIH/NCI, NHLBI, NIDDK; American Heart Association
Baden, 2021^24^; United States; NHS, NHSII, HPFS; Analytic N=209,468; Participant characteristics:; - [underlined: Race and/or Ethnicity]: 95-98% White; - [underlined: SEP]: 100% Nurses and health professionals; - [underlined: Selection:] Excluded participants with a history of CVD or cancer at baseline, missing dietary data, or implausible dietary energy intakes | - DP Age(s): 30 to 55 y at baseline, NHS; Mean age: 50 to 51 y; - 25 to 42 y at baseline, NHS II; Mean age: 36 to 37 y; - 40 to 75 y at baseline, HPFS; Mean age: 53-54 y; - DP(s) examined: Plant-Based Diet Index (PDI); healthful PDI (hPDI); unhealthful PDI (uPDI); - DP Components: PDI: Positive: Vegetables; Potatoes; Legumes; Fruit; Fruit Juices; Nuts; Whole Grains; Refined Grains; Tea and Coffee; Sugar-Sweetened and Artificially Sweetened Beverages; Sweets and Desserts. Negative: Fish or Seafood; Meat; Egg; Miscellaneous Animal Foods; Dairy; Animal Fat; - hPDI: Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Negative: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; - uPDI: Negative: Whole grains; Fruits; Vegetables; Nuts; Legumes; Vegetable oils; Tea/coffee; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; Positive: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; - DP Method(s): Index; Comparisons: Categorical: Quartiles of PDI, hPDI, uPDI | Follow-Up Duration: 26-32 y; PDI vs. total stroke, HR, 95% CI (pooled across NHS, NHSII and HPFS); Q1: REF; Q2: 1.01, 95% CI: 0.93, 1.09; Q3: 0.99, 95% CI: 0.91, 1.07; Q4: 0.97, 95% CI: 0.89, 1.05; Q5: 0.94, 95% CI: 0.86, 1.03 P-trend: 0.15; hPDI vs. total stroke, HR, 95% CI (pooled across NHS, NHSII and HPFS); Q1: REF; Q2: 0.98, 95% CI: 0.90, 1.06; Q3: 0.91, 95% CI: 0.84, 0.99; Q4: 0.89, 95% CI: 0.82, 0.96; Q5: 0.90, 95% CI: 0.83, 0.98; P-trend: 0.002; uPDI vs. total stroke, HR, 95% CI (pooled across NHS, NHSII and HPFS); Q1: REF; Q2: 1.10, 95% CI: 1.01, 1.20; Q3: 1.11, 95% CI: 1.02, 1.20; Q4: 1.18, 95% CI: 1.09, 1.29; Q5: 1.05, 95% CI: 0.96, 1.15; P-trend: 0.19; PDI vs. ischemic stroke, HR, 95% CI (pooled across NHS, NHSII and HPFS); Q1: REF; Q2: 1.03, 95% CI: 0.92, 1.16; Q3: 1.03, 95% CI: 0.92, 1.16; Q4: 1.02, 95% CI: 0.91, 1.16; Q5: 1.04, 95% CI: 0.91, 1.18; P-trend: 0.59; hPDI vs. ischemic stroke, HR, 95% CI (pooled across NHS, NHSII and HPFS); Q1: REF; Q2: 1.05, 95% CI: 0.94, 1.18; Q3: 0.93, 95% CI: 0.83, 1.04; Q4: 0.95, 95% CI: 0.85, 1.08; Q5: 0.92, 95% CI: 0.82, 1.04; P-trend: 0.06; uPDI vs. ischemic stroke, HR, 95% CI (pooled across NHS, NHSII and HPFS); Q1: REF; Q2: 1.07, 95% CI: 0.95, 1.21; Q3: 1.09, 95% CI: 0.97, 1.23; Q4: 1.17, 95% CI: 1.03, 1.32; Q5: 0.96, 95% CI: 0.84, 1.09; P-trend: 0.76; PDI vs. hemorrhagic stroke, HR, 95% CI (pooled across NHS, NHSII and HPFS); Q1: REF; Q2: 1.10, 95% CI: 0.89, 1.37; Q3: 0.98, 95% CI: 0.78, 1.22; Q4: 1.05, 95% CI: 0.83, 1.31; Q5: 1.05, 95% CI: 0.82, 1.33; P-trend: 0.89; hPDI vs. hemorrhagic stroke, HR, 95% CI (pooled across NHS, NHSII and HPFS); Q1: REF; Q2: 1.10, 95% CI: 0.88, 1.38; Q3: 1.05, 95% CI: 0.84, 1.31; Q4: 1.04, 95% CI: 0.83, 1.31; Q5: 0.93, 95% CI: 0.74, 1.18; P-trend: 0.46; uPDI vs. hemorrhagic stroke, HR, 95% CI (pooled across NHS, NHSII and HPFS); Q1: REF; Q2: 1.11, 95% CI: 0.89, 1.39; Q3: 0.99, 95% CI: 0.79, 1.24; Q4: 1.10, 95% CI: 0.88, 1.39; Q5: 0.96, 95% CI: 0.75, 1.23; P-trend: 0.55; Summary: Inverse: hPDI and total stroke; Positive: uPDI (Q2, Q3, Q4) and total stroke; NS/Null: PDI and total stroke; PDI, hPDI, uPDI and ischemic stroke; PDI, hPDI, uPDI and hemorrhagic stroke | - Did not account for: Sex, Age, SEP; - Dietary assessment: Multiple exposure assessment; - Outcome measurement: Stroke sub-type data were missing in 38% of the participants; Medical record abstraction; National Death registry; Probable cases without adequate documentation were included; - Analysis did not adjust for age, sex and SEP may not get total credit either. Findings may not be generalizable since majority of the participants were Whites and health professionals. Stroke subtype data were missing in 38% of the participants and hence the analysis may not have the power. Study did not adjust for multiple testing. robable cases without adequate documentation were included; - Funding: NIH/NHLBI, NIH/NCI, NIH/NIDDK, Manpei Suzuki Diabetes Foundation
Bertoia, 2014^25^; United States; WHI; Observational Study; Analytic N=93,122; Participant characteristics:; - [underlined: Race and/or Ethnicity]: ~84% NHW; ~8% African Americans; 4% Hispanic/Latino; - [underlined: SEP]: 13-21% income <20,000; 16-23% income ≥ $75,000; - [underlined: Selection:] Excluded participants with missing baseline DP, missing race and pulse data who planned to move out of study area or had predicted survival <3y, participating in another trial; or had demetina, drug-dependency, mental illness, or alcoholism; - Self reported CAD: ~7.5%; - Self-reported Hypertension: 66-69%; - self-reported congestive heart failure: ~1% | - DP Age(s): 50 to 79 y at baseline; Mean age: 63.6 y; - DP(s) examined: Mediterranean Diet Score (MDS) [Trichopolou, 2003]; - DASH diet score [Fung, 2008]; - DP Components: Mediterranean: Positive: Vegetables; Fruit, Nuts and legumes; Cereals; Fish; Whole grains; MUFA/SFA. Negative: Red and Processed Meat; Poultry; high-fat dairy. Neutral: Alcohol; - DASH: Positive: Vegetables; Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Sodium; - DP Method(s): Index; Comparisons: Categorical: Quintiles of MDS, DASH | Follow-Up Duration: 10.5 y; CVD mortality; MDS vs. sudden cardiac death, HR, 95% CI; Q1: REF; Q2: 0.81, 95% CI: 0.54, 1.23; Q3: 0.69, 95% CI: 0.47, 1.00; Q4: 0.76, 95% CI: 0.52, 1.11; Q5: 0.67, 95% CI: 0.46, 0.99; P-trend: 0.21; DASH vs. sudden cardiac death, HR, 95% CI; Q1: REF; Q2: 1.09, 95% CI: 0.75, 1.60; Q3: 1.11, 95% CI: 0.75, 1.63; Q4: 0.95, 95% CI: 0.62, 1.45; Q5: 0.86, 95% CI: 0.54, 1.38; P-trend: 0.46; Summary: NS/Null: DASH score & sudden cardiac death; NS/Null: MDS (Q2, Q3, Q4 v. Q1) & sudden cardiac death; Inverse: MDS (Q5 vs. Q1) & sudden cardiac death | - Did not account for: None (all) (for MED), Alcohol (DASH); - Dietary assessment: Multiple exposure assessment; - Outcome measurement: Death records + Medical records +adjudication; - Alcohol was included in the Mediterranean DP, but it was not included in DASH and nor was it adjusted in the model; - Funding: NR
Bhupathiraju, 2022^26^; United States; MASALA; Analytic N=891; Participant characteristics:; - [underlined: Race and/or] [underlined: Ethnicity]:100% South Asian-American; - [underlined: SEP]: ~84-92% Bachelor’s degree; - ~71-75% family income >$75,000; - [underlined: Selection:] Excluded participants with CVD at baselinereporting implausible energy intakes and with missing data; - 100% participants with South Asian ancestry; - ~40% hypertension; - ~79% Controlled hyperlipidemia; - Mean BMI: ~26 kg/m2 | - DP Age(s): 40 to 84 y at baseline; - DP(s) examined: Plant-Based Diet Index (PDI); Healthy Plant-Based Diet Index (hPDI); Unhealthy Plant-Based Diet Index (uPDI); - DP Components: PDI: Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Negative: Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; - hPDI: Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Negative: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; - uPDI: Negative: Whole grains; Fruits; Vegetables; Nuts; Legumes; Vegetable oils; Tea/coffee; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; Positive: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; - DP Method(s): Index; Comparisons: Continuous PDI, hPDI and uPDI | Follow-Up Duration: 5 y; DP vs. TG, mmol/L; PDI: − 0.61 ± 0.97; p-value: 0.53; hPDI: −0.41 [underlined: +] 0.83; p-value: 0.61; uPDI: 0.55 [underlined: +] 0.99; p-value: 0.58; HDL-C, mmol/L; PDI: 0.006 ± 0.006; p-value: 0.31; hPDI: 0.004 ± 0.005; p-value: 0.46; uPDI: 0.004 ± 0.006; p-value: 0.46; LDL-C, mmol/L; PDI: − 0.026 ± 0.021; p-value: 0.20; hPDI: −0.007 ± 0.017; p-value: 0.70; uPDI: 0.007 ± 0.021; p-value: 0.74; Summary: NS/Null: PDI, hPDI, uPDI & TG, HDL-C, LDL-C | - Did not account for: None (all); - Dietary assessment: Single time point measurement of exposure; - Outcome measurement: Measured HDL-C, LDL-C, TG after 12 hour fasting; - Single time point measure at baseline; Unclear if the participants that were lost to f/u are different than those that were F/U; - Funding: NIH, University of San Francisco
Booth, 2016^27^; United States; REGARDS; Analytic N=5709; Participant characteristics:; - [underlined: Race and/or Ethnicity]:; 58% White; 42% Blacks; - [underlined: SEP]:; ~11% < High school:; ~11-29% Income; <$20,000; - [underlined: Selection:] Excluded those >80 y +; with Hx of CVD or End stage renal disease, low or high LDL, or taking statins, or missing data on risk.; - All higher risk of stroke | - DP Age(s): 40 to 79 y at baseline; Mean ages: 61.5-68.3 y; - DP(s) examined: Mediterranean Diet Score (MDS) [Trichopolou, 2003]; - DP Components: Positive: Vegetables; Legumes; Fruit, Nuts; Cereals; Fish; MUFA/SFA. Negative score component: Red and Processed Meat; Dairy Products. Neutral: Alcohol; - DP Method(s): Index; Comparisons: Categorical: quartiles of MDS | Follow-Up Duration: 6 y; Quartiles of MDS vs. atherosclerotic CVD, HR, 95% CI; Q1: REF; Q2, HR: 0.95, 95% CI: 0.70, 1.30; Q3, HR: 0.96, 95% CI: 0.70, 1.32; Q4, HR: 0.76, 95% CI: 0.57, 1.02; P-trend: 0.103; Summary: NS/Null: MDS & CVD-incidence | - Did not account for: Physical activity, Anthropometry, Smoking, Total energy intake; - Dietary assessment: Single time point measurement of exposure; - Outcome measurement: Medical record abstraction + adjudication; - Smoking, Anthropometry, and Physical activity were not adjusted for because they were addressed with primary independent variable (healthy lifestyle score); Single time point measure of exposure; 25% of the participants were missing dietary data and the authors relied on multiple imputations to account for missing data; Unclear if the participants that were excluded from the analysis were different than those that were included in the study; Outcomes were self-reported and adjudicated.; - Funding: NIH
Buijsse, 2015^127^; United States; CARDIA; Analytic N=2596; Participant characteristics:; - [underlined: Race and/or Ethnicity:]; 57% White; 43% Black; - [underlined: SEP:] Education: ~16 y; - [underlined: Selection:] Participants were initially hypertension-free; - 56% female; Mean BMI: 26.9 kg/m2 | - DP Age(s): 18 to 30 y at baseline; Mean age: 35 y; - DP(s) examined: A Priori Diet Quality Score (APDQS); - DP Components: Positive: Vegetables-Green; Vegetables-Yellow; Vegetables-Other; Tomatoes; Beans/Legumes; Fruit; Avocado; Nuts, Seeds; Soy Products; Whole Grains; Fish; Lean fish; Poultry; Low-Fat Dairy; Vegetable Oil; Beer, Wine, Liquor; Tea, Coffee. Negative: Fried potatoes; High-fat meat; Processed meats; Organ meats; Fried Fish/Poultry; High-Fat Dairy; Pastries; Sweets; Desserts; Sugar-sweetened soft drinks; Butter; Fried Foods; Salty Snacks; Sauces. Neutral: Potatoes; Fruit Juices; Refined grains; Eggs; Shellfish; Lean meat; Margarine; Chocolate & Diet Soft Drinks; Meal replacements; Pickled foods; Sugar substitutes; Diet drinks; - DP Method(s): Index; - Comparisons: Categorical: Quartile of APDQS | Follow-Up Duration: 6 y; a priori diet quality score vs. incident hypertension, HR, 95% CI; 1: REF; 2: 0.89, 95% CI: 0.74, 1.08; 3: 0.80, 95% CI: 0.64, 0.99; 4: 0.81, 95% CI: 0.63, 1.04; P-trend: 0.05; Per 12 point increase: 0.90, 95% CI: 0.84, 0.97; Summary: Inverse: a priori diet quality & incident hypertension | - Did not account for: None; - Dietary assessment: Single time point measurement of exposure; - Outcome measurement: SBP, DBP measured thrice and the average of second and third readings were used; SBP>=140 mmHg; DBP >=90 mmHg or use of new hypertensive medication was treated as incident hypertension; - Generalizability may be an issue since only Whites and Blacks were included; SBP was adjusted in the model, possible overadjustment.; - Funding: NIH
Campos, 2019^28^; United States; MESA; Analytic N=4478; Participant characteristics:; - [underlined: Race and/or Ethnicity:]; 40.3% White;; 12.8% Chinese;; 24.6% African Americans;; 22.1% Hispanics; - [underlined: SEP:] 14-19% <High school; - [underlined: Selection:] Excluded those with CVD history, insufficient/unreliable dietary data; - 52% female; - ~43% Hypertension; - Mean BMI: 27 kg/m2 | - DP Age(s): 45 to 84 y; Mean age: 62 y; - DP(s) examined: DASH; - DP Components: DASH: Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Sodium; - DP Method(s): Index; Comparisons: Categorical: Quintiles of DASH score | Follow-Up Duration: 13 y; DASH vs. Incident heart failure HR, 95% CI; Q1: REF; Q2: 1.1, 95% CI: 0.7, 1.8; Q3: 1.1, 95% CI: 0.7, 1.8; Q4: 0.9, 95% CI: 0.5, 1.4; Q5: 0.7, 95% CI: 0.4, 1.2; P-trend: 0.265; Summary: NS/Null: DASH & heart failure;; Additional analyses excluding those older than 75 were inverse and reached significance for Q5 v. Q1 | - Did not account for: Alcohol; - Dietary assessment: Single time point measurement of exposure; - Outcome measurement: Medical record abstraction + adjudication; - Single time point measurement of exposure; - Funding: NIH/NHLBI, NCART, USDA/ARS
Chang, 2022^29^; United States; Southern Community Cohort Study; Analytic N=25,300; Participant characteristics:; - [underlined: Race and/or Ethnicity:] 68% Black; 32% White; - [underlined: SEP:] 69.3% with annual household income <$15,000; 88% <$25k; - 100% participants with Medicare or Medicaid; - [underlined: Selection:] Excluded participants with end-stage renal disease, heart failure, missing DASH score; - Mean BMI: 29.1 kg/m2; - Hypertension: 62.5%; - High cholesterol: 39.9% | - DP Age(s): 47 to 65 y at baseline; Mean age: 54 y; - DP(s) examined: DASH; - DP Components: DASH: Positive: Total vegetables; Legumes/Beans; Total fruits; Total Grains; Negative: Total red meat, poultry, fish; Total dairy products; Sugar/sweets/pastries; E% from fat E% saturated fat; Sodium; - DP Method(s): Index; Comparisons: Continuous (Per 13.3 IQR increase) | Follow-Up Duration: 11 y; DASH score vs. incident heart failure, HR, 95% CI; Overall: 1.00, 95% CI: 0.96, 1.04;; P-value: 0.86; Black women: 1.00, 95% CI: 0.94, 1.06;; P-value: 0.87; Black men: 0.98, 95% CI: 0.91, 1.06;; P-value: 0.62; White women: 1.00, 95% CI: 0.92, 1.08;; P-value: 0.92; White men: 1.07, 95% CI: 0.95, 1.21;; P-value: 0.25; Summary: NS/Null: DASH score and incident heart failure | - Did not account for: Alcohol; - Dietary assessment: Single time point measurement of exposure; - Outcome measurement: Medical record abstraction; - Baseline FFQ only - no repeated measures; Possible mesurement error with covariate measurements; - Funding: NCI/NIH, NHLBI
Chen, 2021^30^; United States; WHI; Analytic N=138,506; Participant characteristics:; - [underlined: Race and/or Ethnicity]:78 - 87% NHW; 7-11% NHB; 2-6% Hispanic; ~4% Other; - [underlined: SEP:] 25%-50% college degree or above; - 30-50% with family income ≥50,000; - [underlined: Selection:] Excluded participants with PAD at baseline, no dietary intake data, missing f/u data on incident PAD; - Mean BMI: ~27 kg/m2; - Hypertension: 36-41% | - DP Age(s): 50 to 79 y at baseline; Mean age: 62 - 64.5 y; - DP(s) examined: aMED; AHEI-2020; DASH; HEI-2015; - DP Components: aMED: Positive: Vegetables; Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA/SFA; Neutral: Red and Processed Meat; Neutral: Alcohol; - AHEI-2010: Positive: Vegetables (not potatoes, French fries); Fruit; Nuts and Soy Protein; Cereal Fiber; White: Red Meat Ratio; PUFA:SFA; Multi-Vitamin Use. Negative: Trans-UFA. Neutral: Alcohol; - DASH: Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Sodium; - HEI-2015: Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; PUFA+MUFA/SFA. Negative: Refined Grains; Added Sugars; SFA; Sodium; - DP Method(s): Index; Comparisons: Categorical: Quartiles of aMED, AHEI-2010, DASH, HEI-2015 | Follow-Up Duration: 18.6 y; aMED vs. PAD, HR, 95% CI; Q1: REF; Q2: 0.80, 95% CI: 0.66, 0.97; Q3: 0.81, 95% CI: 0.69, 0.96; Q4: 0.74, 95% CI: 0.61, 0.91; P-trend: 0.01; Per- SD increment: 0.90, 95% CI: 0.84, 0.97; AHEI-2010 vs. PAD, HR, 95% CI; Q1: REF; Q2: 0.95, 95% CI: 0.81, 1.11; Q3: 0.69, 95% CI: 0.58, 0.83; Q4: 0.79, 95% CI: 0.65, 0.95; P-trend: <0.001; Per-SD increment: 0.87, 95% CI: 0.81, 0.93; DASH; Q1: REF; Q2: 0.75, 95% CI: 0.64, 0.89; Q3: 0.74, 95% CI: 0.62, 0.89; Q4: 0.66, 95% CI: 0.55, 0.80; P-trend: <0.001; Per-SD increment: 0.86, 95% CI: 0.80, 0.92; HEI-2015; Q1: REF; Q2: 0.83, 95% CI: 0.71, 0.98; Q3: 0.81, 95% CI: 0.69, 0.98; Q4: 0.68, 95% CI: 0.56, 0.82; P-trend: <0.001; Per-SD increment: 0.88, 95% CI: 0.83, 0.94 Lower DASH score, below median or <25 1.21, 95% CI: 1.06, 1.38; Stratified by race and/or ethnicity, HR, 95% CI aMED; White: 0.91, 95% CI: 0.84, 0.98; Black: 0.87, 95% CI: 0.73, 1.05; Hispanic/Latino: 0.77, 95% CI: 0.42, 1.41; P-interaction: 0.70; AHEI-2010; White: 0.89, 95% CI: 0.83, 0.96; Black: 0.76, 95% CI: 0.63, 0.91; Hispanic/Latino: 0.76, 95% CI: 0.41, 1.42; P-interaction: 0.12; DASH; White: 0.87, 95% CI: 0.79, 0.93; Black: 0.88, 95% CI: 0.74, 1.05; Hispanic/Latino: 0.83, 95% CI: 0.46, 1.49; P-interaction: 0.92; HEI-2015; White: 0.89, 95% CI: 0.83, 0.96; Black: 0.86, 95% CI: 0.72, 1.02; Hispanic/Latino: 0.93, 95% CI: 0.53, 1.64; P-interaction: 0.87; Summary: Inverse: aMED, AHEI-2010, DASH, HEI-2015 score and PAD; Inverse:; aMED, AHEI-2010, DASH, HEI-2015 & PAD (White);; AHEI-2010 (Black); NS/Null:; aMED, DASH, HEI-2015 & PAD (Black); aMED, AHEI-2010, DASH, HEI-2015 (Hispanic/Latino) | - Did not account for: None (all); - Dietary assessment: Single time point measurement of exposure; - Outcome measurement: Medical record abstraction + adjudication; - Limited only to women - so generalizability may be an issue. Single time point dietary intake at baseline; - Funding: NIH/NHLBI, NIDDK
Chen, 2022^31^; United States; Hispanic Community Health Study/Study of Latinos (Cuban, Dominican, Mexican, Puerto Rican, Central American, and South American); Analytic N=10,293; Participant characteristics:; - [underlined: Race and/or Ethnicity]: 100% Hispanic/Latinos; - [underlined: SEP]: ~37-45% >high school education; - [underlined: Selection]: Excluded participants missing dietary data, implausible total energy intake, and those reporting CVD and cancer at baseline were excluded; ~22-55% Males; - Antihypertensive medication: 13%; - Mean BMI: 29.3 kg/m2 | - DP Age(s): 18 to 74 y, at baseline; Mean age: ~38 - 42 y; - DP(s) examined: Alternate Mediterranean diet score (aMED), Healthy Eating Index (HEI)-2015, healthful Plant-Based Diet Index (hPDI); - DP Components: aMED: Positive: Vegetables (not potatoes); Legumes; Fruit (excluding juices); Nuts; Whole Grains; Fish & shell fish; MUFA/SFA. Negative: Red and Processed Meat. Neutral: Alcohol; - HEI-2015: Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; PUFA+MUFA/SFA. Negative: Refined Grains; Added Sugars; SFA; Sodium; - hPDI: Positive: Vegetables (excl potatoes); Fruits (excl juices); Nuts & Legumes; Whole grains; Vegetable oils; Tea/coffee; Negative: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Animal fats; Dairy; Eggs, Fish/seafood; White meat (poultry & fish/shellfish); Red and processed meat; - DP Method(s): Index; Comparisons: Categorical: Tertiles of DP | Follow-Up Duration: 6 y; aMED vs. incident CVD, RR, 95% CI; T1: REF; T2: 0.88, 95% CI: 0.49, 1.57; T3: 0.52, 95% CI: 0.34, 0.81; P-value: 0.003; Per-SD increment: 0.74; 95% CI: 0.60, 0.91, P-value: 0.005; HEI-2015 vs. incident CVD, RR, 95% CI; T1: REF; T2: 0.86; 95% CI: 0.51, 1.42; T3: 0.65; 95% CI: 0.39, 1.07; P-value: 0.11; Per-SD increment: 0.80; 95% CI: 0.63, 1.00, P-value: 0.05; hPDI (tertiles) vs. incident CVD, RR, 95% CI; T1: REF; T2: 0.60; 95% CI: 0.40, 0.91; T3: 0.59; 95% CI: 0.37, 0.95; P-trend: 0.03; Per-SD increment: 0.74; 95% CI: 0.60, 0.93; P-value: 0.008; Summary: Inverse: aMED, hPDI & incident CVD; NS/Null: HEI-2015 & incident CVD | - Did not account for: None (all); - Dietary assessment: Two consecutive 24 hr recalls; - Outcome measurement: Self-reported; - Diet was measured using 2 24 hr recalls; Outcome self-reported; - Funding: NIH/NHLBI, NIH/NIDDK, NIDCD, NIDCR, ODS
Cheng, 2018^32^; United States; Iowa Women’s Health Study; Analytic N=7064; Participant characteristics:; - [underlined: Race and/or Ethnicity]: >99% White; - [underlined: SEP]: 30-~50% >High school education (stratified by DP); - [underlined: Selection]: Mean BMI: ~27 kg/m2; - History of diabetes, heart disease, cirrhosis: 12-18% | - DP Age(s): 55 to 69 y, at baseline; Mean age: 61.7 y; - DP(s) examined: modified alternate Med Diet Score (mMDS) [Fung, 2005]; - Evolutionary-concordance score [Whalen, 2014, 2016, 2017]; - DP Components: mMDS: Positive: Vegetables (not potatoes), Fruits, Whole grains, Legumes, Fish, Nuts, MUFA: SFA; Negative: Red and processed meats; Other: Alcohol; - Evolutionary-concordance diet score: Positive: Vegetables, Fruits, Lean meats, Fish, Nuts, Fruit and vegetable diversity, Calcium; Negative: Red and processed meats, Sodium, Dairy foods, Grains and starches, Baked goods, SSB, Alcohol; - DP Method(s): Index; Comparisons: Continuous; Categorical, quintiles | Follow-Up Duration: 26 y; mMDS vs. CVD mortality, HR, 95% CI Continuous: 0.99, 95% CI: 0.98, 0.99; Q1: REF; Q2: 0.92, 95% CI: 0.86, 0.99; Q3: 0.94, 95% CI: 0.83, 1.01; Q4: 0.96, 95% CI: 0.83, 1.04; Q5: 0.83, 95% CI: 0.76, 0.90; P-trend: 0.08; E-C vs. CVD mortality, HR, 95% CI; Continuous: 1.00 95% CI: 1.00, 1.00; Q1: REF; Q2: 0.98, 95% CI: 0.90, 1.04; Q3: 0.96, 95% CI: 0.90, 1.04; Q4: 0.97, 95% CI: 0.97, 1.05; Q5: 1.00, 95% CI: 0.92, 1.08 p-trend: 0.85; Summary: NS/Null: mMDS, Evolutionary-concordance & CVD-mortality; Inverse: mMDS (Q5 vs. Q1) & PAD | - Did not account for: None (all); - Dietary assessment: Single time point measurement of exposure; - Outcome measurement: State registry + National Death Index; - Diet assessed only once at baseline (diet assessed in 2004 was not considered because only ~68% were alive at that time); 99% of the participants were White, which could be an issue with generalizability; The study provides minimal data on participants characteristics, inclusion, missingness etc.; - Funding: NCI
Chiuve, 2014^33^; United States; NHS, HPFS; Analytic N=63,706; Participant characteristics:; - [underlined: Race and/or Ethnicity]: Primarily White (Caucasians); - [underlined: SEP]: 100% Nurses, health professionals; - [underlined: Selection]: Excluded those with previously diagnosed CVD, cancer and history of diabetes; - Mean BMI: ~25 kg/m2 | - DP Age(s): 30 to 55 y, NHS; Mean age at baseline: 52 y; - 40 to 75 y, HPFS; Mean age at baseline: 52 y; - DP(s) examined: Diet Composite Score; - DP Components: Diet Composite Score: Fruits, vegetables, Nuts, Cereal Fiber, Red+Processed meat, and SSB; - DP Method(s): Index; Comparisons: Continuous, per 1-pt increase | Follow-Up Duration: 23.9 y; Diet composite score vs. CVD, HR, 95% CI; Women: 0.95, 95% CI: 0.93, 0.97; Men: 0.93, 95% CI: 0.91, 0.95; Summary: Inverse: Diet Composite Score & CVD (Men & women) | - Did not account for: Age, Alcohol, Race and/or ethnicity (mostly Caucasians), Physical activity, Anthropometry: BMI, Smoking, SEP (health professionals), Other: Total E; - Dietary assessment: Multiple exposure assessment; - Outcome measurement: Composite of ischemic CVD that included fatal and non-fatal; Medical record abstraction + adjudication; Death certificates; - Outcome was a composite of ischemic CVD that included fatal and non-fatal; Data was for derivation of an overall lifestyle score; Generalizability may be an issue because the study was restricted primarily to NHW and health professionals.; - Funding: AHA; NIH
Choi, 2021^35^; United States; CARDIA; Analytic N=2621; Participant characteristics:; - [underlined: Race and/or Ethnicity]: 50.7% Blacks; 49.3% White; - [underlined: SEP]: Maximum education attainment ~15y; - [underlined: Selection]: Excluded participants with implausible energy intake, lacked information on physical activity, smoking; - Hypertension: 4%; - Dyslipidemia: 27% | - DP Age(s): 18 to 30 y at baseline; Mean age at f/u: 45y; - DP(s) examined: A Priori Diet Quality Score (APDQS); - DP Components: APDQS: Positive: Vegetables-Green; Vegetables-Yellow; Vegetables-Other; Tomatoes; Beans/Legumes; Fruit; Avocado; Nuts, Seeds; Soy Products; Whole Grains; Fish, fatty not fried; Fish, lean not fried; Poultry; Low-Fat Dairy; Beer, Wine, Liquor; Tea, Coffee;; - Negative: Fried potatoes; High-fat meat; Processed meat; Fried Fish; Fried Poultry; Whole-Fat Dairy; Butter; Candy; Soft drinks; Bakery Desserts; Salty Snacks.; - Neutral: Potatoes; Fruit Juices; Refined grains; Eggs; Shellfish; Margarine; Chocolate & Diet Soft Drinks; Meal replacements; Pickled foods; Soups, Sugar substitutes; - DP Method(s): Index; - Comparisons: Categorical: Quintile of APDQS; 13-yr change in APDQS | Follow-Up Duration: 32 y; APDQS vs. CVD, HR, 95% CI; Q1: REF; Q2: 0.83, 95% CI: 0.60, 1.15; Q3: 0.72, 95% CI: 0.51, 1.03; Q4; 0.79, 95% CI: 0.53, 1.16; Q5: 0.54, 95% CI: 0.32, 0.93; P-trend: 0.018; Each 1-SD increment: 0.81, 95% CI: 0.68, 0.96; APDQS vs. CHD, HR, 95% CI; Q1: REF; Q2: 0.89, 95% CI: 0.54, 1.45; Q3: 0.97, 95% CI: 0.59, 1.61; Q4: 0.69, 95% CI: 0.38, 1.25; Q5: 0.61, 95% CI: 0.30, 1.25; P-trend: 0.15; Each 1-SD increment: 0.83, 95% CI: 0.65, 1.07; APDQS vs. Hypertensive-related CVD, HR, 95% CI; Q1: REF; Q2: 0.74, 95% CI: 0.51, 1.07; Q3: 0.60, 95% CI: 0.39, 0.92; Q4: 0.73, 95% CI: 0.46, 1.16; Q5: 0.50, 95% CI: 0.25, 0.99; P-trend: 0.022; Each 1-SD increment: 0.77, 95% CI: 0.62, 0.96; 13-yr change in APDQS vs. CVD, HR, 95% CI; Q1: REF; Q2: 0.86, 95% CI: 0.49, 1.5; Q3: 0.47, 95% CI: 0.24, 0.92; Q4; 0.75, 95% CI: 0.41,1.35; Q5: 0.36, 95% CI: 0.17, 0.75; P-trend: 0.028; Each 1-SD increment: 0.73, 95% CI: 0.56, 0.97; 13-yr change in APDQS vs. CHD, HR, 95% CI; Q1: REF; Q2: 0.83, 95% CI: 0.37, 1.82; Q3: 0.53, 95% CI: 0.21, 1.32; Q4; 0.77, 95% CI: 0.34, 1.75; Q5: 0.20, 95% CI: 0.06, 0.72; P-trend: 0.076; Each 1-SD increment: 0.69, 95% CI: 0.46, 1.04; 13-yr change in APDQS vs. hypertensive-related; CVD, HR, 95% CI; Q1: REF; Q2: 0.60, 95% CI: 0.32, 1.15; Q3: 0.23, 95% CI: 0.10, 0.54; Q4; 0.44, 95% CI: 0.22, 0.90; Q5: 0.31, 95% CI: 0.14, 0.68; P-trend: 0.003; Each 1-SD increment: 0.61, 95% CI: 0.44, 0.84; Summary: Inverse: APDQS vs. CVD, hypertensive-related CVD; Inverse: APDQS (13-y change) vs. CVD, hypertensive-related CVD; Null: APDQS vs CHD; Null: APDQS (13-y change) vs. CHD | - Did not account for: None (all); - Dietary assessment: Multiple exposure assessment; - Outcome measurement: Self report; Adjudicated only for deaths; - Generalizability may be an issue since only Whites and Blacks were included; Self report; Adjudicated only for deaths; - Funding: NHLBI
Choi, 2022^34^; United States; CARDIA; Analytic N=4701; Participant characteristics:; - [underlined: Race and/or Ethnicity]: 50% Black; 50% White; - [underlined: SEP]: 14.1-17 y Max educational attainment; - [underlined: Selection]: Excluded particiants with missing LDL-C data at year 0, missing covariates, taking lipid-lowering medications until year 5, implausible energy intakes; having CVD, diabetes or hypertension or receiving treatment for those conditions at Y0.; - 55% female | - DP Age(s): 18 to 30 y at baseline; Mean age at baseline: 23-26 y; - DP(s) examined: A Priori Diet Quality Score (APDQS); - DP Components: APDQS: Positive: Vegetables-Green; Vegetables-Yellow; Vegetables-Other; Tomatoes; Beans/Legumes; Fruit; Avocado; Nuts, Seeds; Soy Products; Whole Grains; Fish; Lean fish; Poultry; Low-Fat Dairy; Vegetable Oil; Beer, Wine, Liquor; Tea, Coffee.; - Negative: Fried potatoes; High-fat meat; Processed meats; Organ meats; Fried Fish/Poultry; High-Fat Dairy; Pastries; Sweets; Desserts; Sugar-sweetened soft drinks; Butter; Fried Foods; Salty Snacks; Sauces.; - Neutral: Potatoes; Fruit Juices; Refined grains; Eggs; Shellfish; Lean meat; Margarine; Chocolate & Diet Soft Drinks; Meal replacements; Pickled foods; Sugar substitutes; Diet drinks; - DP Method(s): Index; Comparisons: Continuous; Categorical APDQS | Follow-Up Duration: 32 y; APDQS vs. incident CHD, HR, 95% CI; Q1: REF; Q2: 0.67, 95% CI: 0.4, 1.12; Q3: 0.66, 95% CI: 0.38, 1.15; Q4: 0.63, 95% CI: 0.34, 1.17; Q5: 0.38, 95% CI: 0.17, 0.86; Per-1 SD change: 0.73, 95% CI: 0.55, 0.96; P-for trend: 0.023; APDQS vs. stroke, HR, 95% CI; Q1: REF; Q2: 0.44, 95% CI: 0.24, 0.82; Q3: 0.43, 95% CI: 0.21, 0.85; Q4: 0.61, 95% CI: 0.29, 1.27; Q5: 0.55, 95% CI: 0.21, 1.45; Per-1 SD change: 0.70, 95% CI: 0.50, 0.99; P-for trend: 0.043; Change in APDQS (1 SD increment) vs. change in LDL-C, β, SE; 7 year change: −0.02, 0.01, P-value: 0.09; 13-year change: −0.07, 0.02, P-value: <0.001; 20-year change: −0.05, 0.02, P-value: 0.007; Change in APDQS (1 SD increment) vs. change in non-HDL-C, β, SE; 7 year change: −0.03, 0.01, P-value: 0.019; 13-year change: −0.09, 0.02, P-value: <0.001; 20-year change: −0.06, 0.02, P-value: <0.001; Summary: Inverse: APDQS & incident CHD, stroke; Inverse: Change in APDQS & change in LDL-C (13-year and 20-year change) and non-HDL-C (7 y, 13y and 20 y change) | - Did not account for: None (all); - Dietary assessment: Multiple exposure assessment; - Outcome measurement: Medical record abstraction +adjudication + Death certificate; - Biomarkers measured after 12 hr fasting; - Included only White and Black participants and findings may not be widely generalizable.; - Funding: NHLBI
Chomistek, 2015^36^; United States; NHS; Analytic N=88,940; Participant characteristics:; - [underlined: Race and/or Ethnicity]: Predominantly White; - [underlined: SEP]: 100% Nurses; - [underlined: Selection]: Excluded those with a history of CVD, cancer, or diabetes, at baseline and missing/unreliable/impla usible dietary data, missing BMI or physical activity data. For hypertension and hypercholesterolemia, participants with a diagnosis of HTN or hypercholesterolemia were excluded. | - DP Age(s): 27 to 44 y at baseline; Mean age: ~37 y; - DP(s) examined: Alternative HEI (AHEI)-2010 [Chiuve 2012]; - DP Components: AHEI-2010: Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium; Moderate: Alcohol; - DP Method(s): Index; Comparisons: Categorical: <36 ref, 36-41.9, 42-46,9, 47-52.9, 53+ | Follow-Up Duration: 20 y; AHEI-2010 vs. CHD, HR, 95% CI; <36: REF; 36-41.9: 1.15, 95% CI: 0.86, 1.54; 42-46.9: 1.12, 95% CI: 0.83, 1.51; 47-53.9: 0.89, 95% CI: 0.65, 1.22; 53+: 0.68, 95% CI: 0.48, 0.96 p-trend: 0.003; All, AHEI-2010 vs. CHD, HR, 95% CI (Dichotomous); AHEI<47: REF; AHEI ≥47, 0.69, 95% CI: 0.57, 0.85; No Clinical risk factors, AHEI-2010 vs. CHD, HR, 95% CI; AHEI <47: REF; AHEI ≥47, HR: 0.66, 95% CI: 0.46, 0.96; One or more clinical risk factors, AHEI-2010 vs. CHD, HR, 95% CI; AHEI<47: REF; AHEI ≥47, HR: 0.72, 95% CI: 0.57, 0.92; AHEI-2010 vs. Hypertension, HR, 95% CI; AHEI <47: REF; AHEI ≥47: 0.89, 95% CI: 0.86, 0.92; AHEI-2010 vs. Hypercholesterolemia, HR, 95% CI; AHEI <47: REF; AHEI ≥47: 0.92, 95% CI: 0.90, 0.95; Summary: Inverse: AHEI-2010 & CHD, hypertension and hypercholesterolemia; Inverse: AHEI-2010 (With & without clinical risk factors) | - Did not account for: Physical activity (co-exposure), Anthropometry (co-exposure), Smoking (co-exposure); - Dietary assessment: Multiple exposure assessment; - Outcome measurement: Medical record + partial self-reported (hypertension, hypercholesterolemia); - Physical activity, Anthropometry and Smoking not accounted in the model because they were co-exposures; Generalizability is an issue because participants are 100% nurses and predominantly White. Hypertension and hypercholesterolemia are self-reported and there is a possibility of misclassification; No information on whether partcipants included in the study were similar or different than those that did not participate; Dietary data is collected in 4 year cycles, but unclear if and how it was integrated as a single exposure for this study.; - Funding: NIH
Cuenca-Garcia, 2014^37^; United States; Aerobics Center Longitudinal Study (ACLS); Analytic N=12,449; Participant characteristics:; - [underlined: Race and/or Ethnicity]: NHW: >95%; - [underlined: SEP]: Middle-upper SES, Well-educated; - [underlined: Selection]: Excluded those with Hx of CVD, Cx; failed exercise test, < 1y f/u; missing/implausible data.; - 78% Male; - Hypercholesterolemia: ~30%; - Hypertension: 27% | - DP Age(s): 20 to 84 y, at baseline; Mean age for men: 46.9 y; Mean age for women: 45.5 y; - DP(s) examined: Ideal Diet Index (IDI) [Cuenca-Garcia, 2014]; - Diet Quality Index (DQI) [Patterson, 1994]; - Mediterranean Diet Score (MDS) [Trichopolou, 2003]; - DP Components:; - IDI: Positive: Vegetables and Fruit; Legumes, Nuts, and Seeds; Whole Grains; Fish. Negative: Processed Meat; Added Sugar; SFA; Sodium; - DQI: Positive: Vegetables and Fruit; Breads, Cereal, and Legumes; Calcium. Negative: Total Fat; SFA; Cholesterol; Protein; Sodium; - MDS: Positive: Vegetables; Legumes; Fruit, Nuts; Cereals; Fish; MUFA/SFA. Negative: Red and Processed Meat; Dairy Products. Neutral: Alcohol; - DP Method(s): Index; Comparisons: Categorical, quartiles | Follow-Up Duration: 11.6 y; CVD mortality; IDI vs. CVD mortality, HR, 95% CI; Q1: REF; Q2: 1.30, 95% CI: 0.76, 2.21; Q3: 0.86, 95% CI: 0.47, 1.56; Q4: 1.02, 95% CI: 0.55, 1.90; P-trend: 0.472; DQI vs. CVD mortality, HR, 95% CI; Q1: REF; Q2: 0.86, 95% CI: 0.47, 1.56; Q3: 0.86, 95% CI: 0.48, 1.52; Q4: 1.12, 95% CI: 0.62, 2.02; P-trend: 0.719; MDS vs. CVD mortality, HR, 95% CI; Q1: REF; Q2: 1.34, 95% CI: 0.69, 2.63; Q3: 1.38, 95% CI: 0.76, 2.50; Q4: 1.07, 95% CI: 0.53, 2.17 P-trend: 0.626; SBP; IDI, mean diff (SE); Q1, 120.2 (0.22); Q2, 119.6 (0.21); Q3, 119.8 (0.24); Q4, 119.9 (0.32); p-value: 0.350; MDS, mean diff (SE); Q1, 120.3 (0.25); Q2, 120.1 (0.26); Q3, 119.7 (0.19); Q4, 119.6 (0.29); p-value: 0.129; DQI, mean diff (SE); Q1, 120.6 (0.26); Q2, 120 (0.24); Q3, 119.3 (0.22); Q4, 119.9 (0.25); p-value: 0.002; DBP; IDI, mean diff (SE); Q1, 80.8 (0.15); Q2, 80.1 (0.15); Q3, 80.1 (0.17); Q4, 79.5 (0.23); p<0.001; MDS, mean diff (SE); Q1, 81.0 (0.18); Q2, 80.5 (0.19); Q3, 80.1 (0.13); Q4, 79.4 (0.2); p<0.001; DQI, mean diff (SE); Q1, 81.3 (0.18); Q2, 80.5 (0.17); Q3, 79.9 (0.15); Q4, 79.5 (0.17); p<0.001; Summary: NS/Null: IDI, DQI, MDS scores & CVD-mortality; NS/Null: IDI, MDS & SBP; Inverse: IDI, DQI, MDS & DBP; Inverse: DQI & SBP | - Did not account for: Anthropometry; - Dietary assessment: Single time point measurement of exposure; - Outcome measurement: BP measured using AHA protocol; - Significant difference between population included (n=12449) and excluded (n=2906) in age, sex, total cholesterol, BP, hypercholesterolemia, HTN; Anthropometry not adjusted for; Single time point measurement of exposure (at baseline); - Funding: NIH; Coca-Cola; Spanish Grants from the Ministry of Economy and Competitiveness
Dai, 2016^38^; United States; NHLBI Twin Study; Analytic N=910; Participant characteristics:; - [underlined: Race and/or Ethnicity]: 100% White; - [underlined: SEP]: Mean education: 13 y; - [underlined: Selection]: Excluded participants with no dietary data available, implausible energy intakes; 100% male; - Mean BMI: 25.8 kg/m2 | - DP Age(s): 42 to 55 y, at baseline; Mean age: 48 y; - DP(s) examined: Moderation-quantified healthy diet (MQHD);; - alternative MQHD (aMQHD);; - Mediterranean Diet Score; - DP Components: MQHD: Positive: Vegetables; Potatoes; Fruit; Grains; Fish and Shellfish; Poultry; Red Meat; Eggs; Dairy Products; Unsaturated Fatty Acids: SFA; Fried Foods: Non-Fried Foods; Alcohol; - aMQHD: Positive: Vegetables; Potatoes; Fruit; Nuts; Grains; Fish and Shellfish; Poultry; Red Meat; Eggs; Lamb or Veal; White: Red Meat; Dairy Products; Skimmed Milk; Ice Cream: Dairy Products; Unsaturated Fatty Acids: SFA; Fried Foods: Non-Fried Foods; Alcohol; - MDS: Positive: Vegetables; Legumes; Fruit, Nuts; Cereals; Fish; MUFA/SFA. Negative: Red and Processed Meat; Dairy Products. Neutral: Alcohol; - DP Method(s): Index; Comparisons: Continuous (per 10-unit increment) of MQHD, aMQHD, MDS | Follow-Up Duration: 40 y; CVD mortality; MQHD vs. CHD mortality, HR, 95% CI (Overall); Per 10-unit increment: 0.76, 95% CI: 0.66, 0.88; P-value: 0.0003; MQHD vs. CVD mortality, 95% CI; HR: 0.87, 95% CI: 0.79, 0.96; P-value: 0.004; Within-pair association; MQHD vs. CHD mortality, HR, 95% CI; Per 10-unit increment: 0.79, 95% CI: 0.64, 0.96; P-value: 0.02; MQHD vs. CVD mortality, HR, 95% CI; Per 10-unit increment: 0.87, 95% CI: 0.76, 0.998; P-value: 0.047; Between-pair association; MQHD vs. CHD mortality, HR, 95% CI; Per 10-unit increment: 0.74, 95% CI: 0.61, 0.90; P-value: 0.003; MQHD vs. CVD mortality, HR, 95% CI; Per 10-unit increment: 0.87, 95% CI: 0.77, 0.99; P-value: 0.03; MQHD vs. CHD mortality, HR (Q4 vs. Q1), 95% CI; HR: 0.62, 95% CI: 0.42, 0.91; P-value: 0.014; aMQHD vs. CHD mortality, HR (Q4 vs. Q1), 95% CI; HR: 0.68, 95% CI: 0.48, 0.96; P-value: 0.03; Overall; aMQHD vs. CHD mortality, HR, 95% CI; Per 10-unit increment: 0.80, 95% CI: 0.68, 0.93; P-value: 0.004; aMQHD vs. CVD mortality, HR, 95% CI; Per 10-unit increment: 0.90, 95% CI: 0.81, 0.99; P-value: 0.03; Within-pair association; aMQHD vs. CHD mortality, HR, 95% CI; Per 10-unit increment: 0.78, 95% CI: 0.63, 0.97; P-value: 0.03; aMQHD vs. CVD mortality, HR, 95% CI; Per 10-unit increment: 0.89, 95% CI: 0.77, 1.02; P-value: 0.098; Between-pair association; aMQHD vs. CHD mortality, HR, 95% CI; Per 10-unit increment: 0.81, 95% CI: 0.67, 0.995; P-value: 0.045; aMQHD vs. CVD mortality, HR, 95% CI; Per 10-unit increment: 0.91, 95% CI: 0.80, 1.03; P-value: 0.13; Overall: Diet scores without alcohol as a score component; MQHD vs. CHD mortality, HR, 95% CI; Per 10-unit increment: 0.80, 95% CI: 0.68, 0.93; P-value: 0.004; MQHD vs. CVD mortality, HR, 95% CI; Per 10-unit increment: 0.87, 95% CI: 0.79, 0.97; P-value: 0.008; aMQHD vs. CHD mortality, HR, 95% CI; Per 10-unit increment: 0.84, 95% CI: 0.72, 0.99; P-value: 0.03; aMQHD vs. CVD mortality, HR, 95% CI; Per 10-unit increment: 0.91, 95% CI: 0.82, 1.01; P-value: 0.06; Within-pair association: Diet scores without alcohol as a score component; MQHD vs. CHD mortality, HR, 95% CI; Per 10-unit increment: 0.81, 95% CI: 0.66, 1.002; P-value: 0.051; MQHD vs. CVD mortality, HR, 95% CI; Per 10-unit increment: 0.87, 95% CI: 0.76, 1.01; P-value: 0.07; aMQHD vs. CHD mortality, HR, 95% CI; Per 10-unit increment: 0.80, 95% CI: 0.64, 0.99; P-value: 0.049; aMQHD vs. CVD mortality, HR, 95% CI; Per 10-unit increment: 0.90, 95% CI: 0.77, 1.04; P-value: 0.17; Overall; MDS vs. CHD mortality, HR, 95% CI; Per 2-unit increment: 0.86, 95% CI: 0.75, 0.98; P-value: 0.03; MDS vs. CVD mortality, HR, 95% CI; Per 2-unit increment: 0.91, 95% CI: 0.83, 0.998; P-value: 0.045; Within-pair association; MDS vs. CHD mortality, HR, 95% CI; Per 2-unit increment: 0.84, 95% CI: 0.70, 1.02; P-value: 0.07; MDS vs. CVD mortality, HR, 95% CI; Per 2-unit increment: 0.91, 95% CI: 0.81, 1.03; P-value: 0.15; Between pair-association; MDS vs. CHD mortality, HR, 95% CI; Per 2-unit increment in diet score: 0.87, 95% CI: 0.72, 1.05; P-value: 0.14; MDS vs. CVD mortality, HR, 95% CI; Per 2-unit increment in diet score: 0.91, 95% CI: 0.81, 1.03; P-value: 0.12; MDS (Q4 vs. Q1) vs. CHD mortality, HR, 95% CI; HR: 0.75, 95% CI: 0.54, 1.04; P-value: 0.08; MDS (Q4 vs. Q1) vs. CHD mortality, HR, 95% CI; HR: 0.61, 95% CI: 0.41, 0.90; P-value: 0.013; Summary: Inverse: MQHD & CHD, CVD mortality (per 10-pt and by quartile; overall, within-, and between-pairs); Inverse: aMQHD & CHD mortality (per 10-pt and by quartile; overall, within-, and between-pairs); Inverse: aMQHD & CVD mortality (per 10-pt and by quartile; overall); Inverse: MQHD, aMQHD without alcohol & CHD, CVD mortality (overall); Inverse: aMQHD without alcohol & CHD mortality (within-pair); Inverse, NS: MQHD without alcohol & CHD mortality (within-pair); Inverse: MDS & CHD, CVD mortality (overall); Null: MQHD & aMQHD without alcohol & CVD mortality (within-pair); Null: aMQHD & CVD mortality (per 10-pt; within- and between-pairs); Null: MDS & CHD, CVD mortality (per 2-unit increment, by quartile, within- and between-pairs) | - Did not account for: Physical activity; - Dietary assessment: Single time point measurement of exposure; - Outcome measurement: National Death Index, death certificates; - Generalizability may be an issue since the participants were 100% white, males; Physical activity data was not collected and hence was not accounted for. Single time point intake data collection; - Funding: American Heart Association, NHLBI
Del Gobbo, 2015^39^; United States; Cardiovascular Health Study; Analytic N=4490; Participant characteristics:; - [underlined: Race and/or Ethnicity]:89% Caucasians; 11% African Americans; - [underlined: SEP]:; - > High school: 26.3% - 44.8% (when stratified by quartiles of DP); - Income <25,000: 52.8 - 70.3% (when stratified by DP quartiles); - [underlined: Selection:] Excluded participants with prevalent HF, mitral or aortic regurgitation, missing/implausible data. Participants with prevalent hypertension, diabetes and CHD were included; 61% participants were women; - Prevalent hypertension: ~41%; - CHD: 16%; - >50% with overweight/Obesity | - DP Age(s): ≥65 y at baseline; Mean age: 72 y; - DP(s) examined: Alternative HEI (AHEI)-2010 [Chiuve 2012]; - DASH Score [Fung 2008];; - DP Components: AHEI: Positive: Vegetables (not potatoes, French fries); Fruit; Nuts and Soy Protein; Cereal Fiber; White: Red Meat Ratio; PUFA:SFA; Multi-Vitamin Use. Negative: Trans-UFA. Neutral: Alcohol; - DASH: Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Sodium; - AHA-2020: Positive: Fruits & vegetables (excluding potatoes); Fish; Fiber-rich whole grains; Nuts, legumes & seeds; Negative: Sodium; Sugar-sweetened beverages; Processed meats, and Saturated fat; - Biologic: Positive: Fruits; Vegetables; Whole grains; Fish/seafood; Nuts/seeds, PUFA/SF ratio; Negative: Red & processed meats; SSB; Trans fat; Sodium; - DP Method(s): Index; Comparisons: Categorical: quintiles of dietary pattern | Follow-Up Duration: 21.5 y; DASH vs. HF, HR, 95% CI; Q1: REF; Q2: 1.11, 95% CI: 0.95, 1.31; Q3: 1.06, 95% CI: 0.90, 1.26; Q4: 1.19, 95% CI: 1.00, 1.41; Q5: 1.05, 95% CI: 0.88, 1.26; P-trend: 0.36; Effect Modification:; Age:; <72 y: 1.00, 95% CI: 0.76, 1.32; ≥ 72y: 0.96, 95% CI: 0.74, 1.25; p-value: 0.82; Sex:; M: 0.93, 95% CI: 0.70, 1.24; F: 1.17, 95% CI: 0.91, 1.51; p-value: 0.44; Race:; Caucasian: 1.08, 95% CI: 0.89, 1.31; African-American: 0.89, 95% CI: 0.50, 1.60; p-value: 0.42; BMI:; <25: 1.07, 95% CI: 0.79, 1.46; ≥ 25: 1.03, 95% CI: 0.82, 1.29; p-value: 0.70; AHEI vs. HF, HR, 95% CI; Q1: REF; Q2: 1.01, 95% CI: 0.86, 1.19; Q3: 1.01, 95% CI: 0.85, 1.19; Q4: 1.00, 95% CI: 0.85, 1.20; Q5: 0.90, 95% CI: 0.74, 1.09; P-trend: 0.33; Effect Modification:; Age:; <72 y: 0.81, 95% CI: 0.61, 1.08; ≥ 72y: 0.89, 95% CI: 0.68, 1.18; p-value: 0.34; Sex:; M: 0.77, 95% CI: 0.57, 1.03; F: 0.99, 95% CI: 0.76, 1.29; p-value: 0.20; Race:; Caucasian: 0.89, 95% CI: 0.73, 1.09; African-American: 0.98, 95% CI: 0.55, 1.73; p-value: 0.32; BMI:; <25: 0.68, 95% CI: 0.50, 0.93; ≥ 25: 1.03, 95% CI: 0.81, 1.31; p-value: 0.10; AHA-2020 vs. HF, HR, 95% CI; Q1: REF; Q2: 1.04, 95% CI: 0.88, 1.22; Q3: 1.15, 95% CI: 0.97, 1.35; Q4: 1.05, 95% CI: 0.89, 1.25; Q5: 0.96, 95% CI: 0.80, 1.15; P-trend: 0.88; Effect Modification:; Age:; <72 y: 0.79, 95% CI: 0.60, 1.05; ≥ 72 y: 1.02, 95% CI: 0.78, 1.32; p-value: 0.21; Sex:; M: 0.77, 95% CI: 0.57, 1.03; F: 0.94, 95% CI: 0.72, 1.22; p-value: 0.32; Race:; Caucasian: 1.00, 95% CI: 0.84, 1.19; African-American: 0.57, 95% CI: 0.28, 1.13; p-value: 0.07; BMI:; <25: 0.93, 95% CI: 0.69, 1.26; ≥ 25: 0.95, 95% CI: 0.76, 1.20; p-value: 0.64; Biologic Pattern vs. HF, HR, 95% CI; Q1: REF; Q2: 1.18, 95% CI: 1.00, 1.39; Q3: 1.05, 95% CI: 0.88, 1.24; Q4: 1.08, 95% CI: 0.91, 1.28; Q5: 0.99, 95% CI: 0.82, 1.19; P-trend: 0.62; Effect Modification:; Age:; <72 y: 1.03, 95% CI: 0.78, 1.36; ≥ 72 y: 0.85, 95% CI: 0.69, 1.11; p-value: 0.36; Sex:; M: 0.98, 95% CI: 0.75, 1.29; F: 0.95, 95% CI: 0.71, 1.27; Race:; Caucasian: 0.99, 95% CI: 0.84, 1.25; African-American: 0.98, 95% CI: 0.52, 1.84; p-value: 0.80; BMI:; <25: 0.75, 95% CI: 0.54, 1.01; ≥ 25: 1.15, 95% CI: 0.91, 1.45; p-value: 0.18; Summary: NS/Null: DASH, AHEI, AHA-2020, Biologic, & HF. No effect modification by age, sex, race and BMI | - Did not account for: None (all); - Dietary assessment: Multiple exposure assessment; - Outcome measurement: Medical record abstraction + adjudication; - The study may not be entirely generalizable because the study primarily includes White participants (~89% white; 11% AA). Also it is 100% older participants; - Funding: NHLBI; NINDS; NIA
Djousse, 2018^40^; United States; Million Veteran Program; Analytic N=153,802; Participant characteristics:; - [underlined: Race and/or Ethnicity]:81.6% Whites and 10.8% Blacks; - [underlined: SEP]: 100% veterans; - [underlined: Selection:] All veterans, free of CAD at baseline; - Mean BMI: ~29 kg/m2; - ~51% Statin use; - 59% Hypertension | - DP Age(s): Mean age: 64 y at baseline; - DP(s) examined: modified DASH Score [Fung 2008]; - DP Components: Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages [did not collect data on sodium]; - DP Method(s): Index; Comparisons: Categorical: Quintiles of DASH score | Follow-Up Duration: 2.8 y; DASH vs. MI, HR, 95% CI; Q1: REF; Q2: 0.91, 95% CI: 0.84, 0.99; Q3: 0.87, 95% CI: 0.80, 0.95; Q4: 0.86, 95% CI: 0.79, 0.94; Q5: 0.80, 95% CI: 0.73, 0.87; p<0.0001; DASH vs. Total CAD (MI, CAD mortality, CABG, PTCA), HR, 95% CI; Q1: REF; Q2: 0.93, 95% CI: 0.85, 1.01; Q3: 0.88, 95% CI: 0.81, 0.96; Q4: 0.87, 95% CI: 0.80, 0.95; Q5: 0.82, 95% CI: 0.75, 0.89; p<0.0001; Summary: Inverse: DASH & MI, Total CAD | - Did not account for: Other: Total E; SEP; - Dietary assessment: Single time point measurement of exposure; - Outcome measurement: Medical record abstraction; - Single time-point dietary measurement; DASH score did not include sodium. SEP not accounted for in the models; Unclear whether participants that were included were similar or different than those that were not.; - Funding: Veterans Health Administration
Du, 2021^41^; United States; ARIC Study; Analytic N=13,548; Participant characteristics:; - [underlined: Race and/or Ethnicity]: 74% White; 26% Black; - [underlined: SEP]: > High school: ~43%-49% (when staratified by quartiles); - [underlined: Selection:] Excluded participants with implausible energy intake, history of CAD, missing >10 items on FFQ and missing baseline covariates; - Women: 56%; - Overweight/Obesity: ~66%; - Hypertension: 28% | - DP Age(s): 45 to 65 y; Mean age at baseline: ~54y; - DP(s) examined: Ultraprocessed food consumption; - DP Components: UPF: Dairy products (ice cream; fats and oils: margarine); Meats (hamburgers, hot dogs, processed meats (sausage, salami, bologna), beef, pork, or lamb in dishes); Sugary products (chocolate bars or pieces (Hershey’s, plain M&M’s, Snickers, Reese’s), candy without chocolate); Bakery goods (ready-made pie, donuts, biscuits, or cornbread); Danish pastry, sweet roll, coffee cake, croissant, cookies, cake, or brownie; Cereals (cold breakfast cereal; fried foods: potato chips or corn chips, French fried potatoes, food fried away from home); Beverages (orange or grapefruit juice, low calorie and regular soft drinks, fruit-flavored punch or noncarbonated beverages (lemonade, Kool-Aid, Hawaiian Punch)); liquor: hard liquor.; - DP Method(s): Index; Comparisons: Categorical: Quartiles of UPF | Follow-Up Duration: 27 y; UPF vs. CAD, HR, 95% CI; Q1: REF; Q2: 1.05, 95% CI: 0.92, 1.19; Q3: 1.08, 95% CI: 0.95, 1.23; Q4: 1.19, 95% CI: 1.05, 1.35; Stratified by sex, Q4 vs. Q1, HR, 95% CI; Male: 1.16, 95% CI: 0.98, 1.37; Female: 1.15, 95% CI: 0.95, 1.39; P-interaction: 0.88; Stratified by race, Q4 vs. Q1, HR, 95% CI; Black: 1.30, 95% CI: 1.01, 1.69; White: 1.18, 95% CI: 1.02, 1.36; P-interaction: 0.14; Stratified by BMI (kg/m2), Q4 vs. Q1, HR, 95% CI; <25: 1.20, 95% CI: 0.93, 1.53; 25-30: 1.09, 95% CI: 0.90, 1.31; >30: 1.24, 95% CI: 0.99, 1.57; Summary: Direct/Positive: UPF (Q4 vs. Q1) & CAD (Overall, Black, White); NS/Null: UPF & CAD (Q3, Q2 vs. Q1); NS/Null: UPF & CAD, stratified by sex, BMI | - Did not account for: None (all); - Dietary assessment: Multiple exposure assessment; - Outcome measurement: Medical record abstraction + adjudication +Death certificates; - Findings may not be generalizable since most participants were Whites or Blacks and other race/ethnicities were excluded. The classification of the exposure (UPF) was not very clear. The authors also document that the FFQ was not designed to capture UPF intake and hence some of the foods such as energy bars, sports drinks were not included. Authors also acknowledge possible misclassfication of the exposure because of lack of detailed information on food preparation and brands. NOVA system lacks rigorous level of processing definition and classification criteria. Single time point measure of diet with FFQ; - Funding: NHLBI/NIH, NIDDK
Fan, 2023^42^; United States; NHANES; Analytic N=8301; Participant characteristics:; - [underlined: Race and/or Ethnicity]: Mexican American: 7.9%; - [underlined: SEP]: Poverty to income ratio: 2.9; College graduate or above: 23.7%; - [underlined: Selection:] Excluded participants without omplete data of diet, physical activity, PHQ9 and mortality; - 100% MetS; - Female: 55.1% | - DP Age(s): Mean age: 56.7 y; - DP(s) examined: alternative Mediterranean diet index; - DP Components: aMED: Positive: Fruits, vegetables, whole grains, legumes, nuts, fish, the ratio of monounsaturated to saturated fat; Negative: red and processed meat; Moderation: alcohol; - DP Method(s): Index; Comparisons: Categorical: aMED score (below median aMED or HaMED-non S as refs) | Follow-Up Duration: 6.3 y; aMED vs. CVD mortality; aMED (Below Median): REF; aMED (Median): 0.71, 95% CI: 0.52, 0.98; p-value: 0.03; aMED (Above Median): 0.65, 95% CI: 0.49, 0.87; p-value< 0.001; High aMED without sedentary behavior (HaMED-non S) vs. CVD mortality; HaMED-non S: REF; Medium aMED-non S: 1.01, 95% CI: 0.53, 1.92, P-value: 0.99; Low aMED-non S: 1.34, 95% CI: 0.81, 2.21, p-value: 0.26; HaMED-S: 1.43, 95% CI: 0.78, 2.59, p-value: 0.25; Medium aMED-S: 2.04, 95% CI: 1.12, 3.73, p-value: 0.02; Low aMED-S: 2.91, 95% CI: 1.77, 4.79, p-value: <0.001; Summary: Inverse: aMED score (at or above vs. below median) & CVD mortality | - Did not account for: None (all KC); TEI; - Dietary assessment: Two consecutive 24 hr recalls; - Outcome measurement: National Death Index; - Total energy intake not accounted for; Two consequent 24 hr recalls; - Funding: NSF China
Fung, 2016^44^; United States; NHS, NHS II, HPFS; Analytic N=207,041; Participant characteristics:; - [underlined: Race and/or Ethnicity]: NR (mostly Whites); - [underlined: SEP]: 100% Nurses, health professionals; - [underlined: Selection:] Excluded those with MI/Stroke, missing BMI, and missing dietary data or reporting extreme dietary data (<500 kcal or >3500 kcal). | - DP Age(s): 27 to 75 y, at baseline; - DP(s) examined: Food Quality Score (FQS) [Fung, 2016]; - DP Components: FQS: Positive: Vegetables,Fruit, Nuts and Legumes, Whole grains, Yogurt; Coffee; Negative: Red meats; Processed Meats; Desserts and ice cream; Refined grains; Potatoes; Potato chips; Fried foods prepared away from home; Sugar-sweetened Beverages; - DP Method(s): Index; Comparisons: Categorical: deciles | Follow-Up Duration: 28 y; CVD mortality; FQS vs. Total CHD in pooled cohorts (NHS, NHS-II, HFPS), RR, 95% CI; D1: REF; D2: 0.87, 95% CI: 0.79, 0.97; D3: 0.86, 95% CI: 0.78, 0.96; D4: 0.90, 95% CI: 0.82, 1.00; D5: 0.82, 95% CI: 0.73, 0.91; D6: 0.80, 95% CI: 0.72, 0.89; D7: 0.80, 95% CI: 0.72, 0.89; D8: 0.73, 95% CI: 0.66, 0.82; D9: 0.69, 95% CI: 0.61, 0.77; D10: 0.61, 95% CI: 0.54, 0.69; P-trend: <0.001; FQS vs. Non-fatal CHD in pooled cohorts (NHS, NHS-II, HFPS), RR, 95% CI; D1: REF; D2: 0.84, 95% CI: 0.74, 0.95; D3: 0.88, 95% CI: 0.78, 1.00; D4: 0.88, 95% CI: 0.78, 1.00; D5: 0.75, 95% CI: 0.66, 0.85; D6: 0.76, 95% CI: 0.66, 0.86; D7: 0.78, 95% CI: 0.68, 0.89; D8: 0.68, 95% CI: 0.60, 0.78; D9: 0.67, 95% CI: 0.58, 0.77; D10: 0.56, 95% CI: 0.49, 0.65; p-trend<0.001; FQS vs. total CAD in pooled cohorts (NHS, NHSII, HFPS) RR, 95% CI; BMI <25; Q1: REF; Q2: 0.90, 95% CI: 0.79, 1.02; Q3: 0.85, 95% CI: 0.75, 0.97; Q4: 0.77, 95% CI: 0.67, 0.87; Q5: 0.61, 95% CI: 0.53, 0.69; P-trend: <0.001; BMI ≥ 25; Q1: REF; Q2: 0.97, 95% CI: 0.89, 1.07; Q3: 0.88, 95% CI: 0.80, 0.97; Q4: 0.87, 95% CI: 0.78, 0.96; Q5: 0.78, 95% CI: 0.70, 0.87; P-trend: <0.001; P-heterogeneity: 0.006; Physical activity (METs<median); Q1: REF; Q2: 0.95, 95% CI: 0.87, 1.03; Q3: 0.87, 95% CI: 0.80, 0.95; Q4: 0.83, 95% CI: 0.76, 0.92; Q5: 0.76, 95% CI: 0.69, 0.84; P-trend: <0.001; Physical activity (METs ≥ median); Q1: REF; Q2: 0.91, 95% CI: 0.79, 1.05; Q3: 0.79, 95% CI: 0.68, 0.92; Q4: 0.74, 95% CI: 0.64, 0.86; Q5: 0.52, 95% CI: 0.45, 0.61; P-trend: <0.001; P-heterogeneity: 0.17; Smoking status (Nonsmoker); Q1: REF; Q2: 0.93, 95% CI: 0.85, 1.01; Q3: 0.85, 95% CI: 0.78, 0.93; Q4: 0.82, 95% CI: 0.75, 0.90; Q5: 0.68, 95% CI: 0.62, 0.74; P-trend: <0.001; Smoking status (Current smoker); Q1: REF; Q2: 1.06, 95% CI: 0.89, 1.26; Q3: 0.97, 95% CI: 0.80, 1.17; Q4: 0.86, 95% CI: 0.70, 1.06; Q5: 0.85, 95% CI: 0.67, 1.09; P-trend: 0.006; P-heterogeneity: 0.33; Family history of MI - No; Q1: REF; Q2: 0.96, 95% CI: 0.87, 1.06; Q3: 0.85, 95% CI: 0.77, 0.94; Q4: 0.84, 95% CI: 0.76, 0.94; Q5: 0.71, 95% CI: 0.64, 0.80; P-trend: <0.001; Family history of MI - Yes; Q1: REF; Q2: 0.95, 95% CI: 0.85, 1.06; Q3: 0.89, 95% CI: 0.80, 1.00; Q4: 0.83, 95% CI: 0.73, 0.93; Q5: 0.69, 95% CI: 0.61, 0.78; P-trend: <0.001; P-heterogeneity: 0.99; Summary: Inverse: FQS & CHD mortality, MI mortality, fatal MI; Inverse: FQS & total CHD, nonfatal CHD, total CAD (stratified by BMI, physical activity, smoking status and family history of MI) | - Did not account for: SEP; - Dietary assessment: Multiple exposure assessment; - Outcome measurement: Medical record abstraction + probable cases + National Death Index; - Generalizability may be questionable because participants were mostly Whites, were nurses or health professionals; Multiple comparisons not accounted for. Probable cases were included as part of the outcome; - Funding: NIH
Fung, 2018^43^; United States; NHS, NHS II, HPFS; Analytic N=212,142; Participant characteristics:; - [underlined: Race and/or Ethnicity]: NR (but mostly Whites); - [underlined: SEP]: 100% Nurses, health professionals; - [underlined: Selection:] Excluded participants with a history of CHD, stroke and implausible energy intake. Excluded participants that did not return FFQ.; - Mean BMI: 24-25 kg/m2; Current smokers: ~8-35% | - DP Age(s): 43 to 63 y at baseline, NHS I; - 40 to 75 y at baseline, HPFS; - 27 to 44 y at baseline, NHS II; - DP(s) examined: Food Group Index (FGI);; - Minimal Diet Diversity Score for Women (MDDW);; - Prime Diet Quality Score (PDQS); - DP Components: FGI: Positive: Vitamin A rich fruits and vegetables; Other fruits and vegetables; Legumes and nuts; Meat, poultry, fish; Eggs; Dairy; Grains, roots and tubers; Added fats/oils; - MDDW: Positive: Vitamin A rich fruits and vegetables; Dark green, leafy vegetables; Other fruits and vegetables; Legumes and nuts; Meat, poultry, fish; Eggs; Dairy; Grains, roots and tubers; - PDQS: Positive: Vitamin A rich fruits and vegetables; Dark green, leafy vegetables; Carrots; Citrus fruits; Other fruits and vegetables; Legumes and nuts; Eggs; Dairy; Oils; Negative: Potatoes; Fried foods away from home; Sweets and ice cream; Sweetened beverage; Moderate: Meat, poultry, fish; Grains, roots and tubers; - DP Method(s): Index; Comparisons: Continuous, Categorical: quintiles (FGI, MDDW, PDQS) | Follow-Up Duration: 28 y; FGI vs. total IHD, RR, 95% CI; NHS I; Q1: REF; Q2: 0.94, 95% CI: 0.79, 1.13; Q3: 0.97, 95% CI: 0.81, 1.16; Q4: 0.90, 95% CI: 0.75, 1.09; Q5: 0.94, 95% CI: 0.74, 1.19; 1-point increase: 0.96, 95% CI: 0.92, 1.01; HPFS; Q1: REF; Q2: 0.91, 95% CI: 0.78, 1.06; Q3: 0.91, 95% CI: 0.78, 1.06; Q4: 0.93, 95% CI: 0.79, 1.10; Q5: 1.04, 95% CI: 0.86, 1.27; 1- point increase: 1.01, 95% CI: 0.97, 1.05; NHS II; Q1: REF; Q2: 1.06, 95% CI: 0.78, 1.45; Q3: 0.91, 95% CI: 0.65, 1.27; Q4: 0.83, 95% CI: 0.56, 1.24; Q5: -; 1- point increase: 0.91, 95% CI: 0.81, 1.02; MDDW vs. total IHD, RR, 95% CI; NHS I; Q1: REF; Q2: 0.97, 95% CI: 0.83, 1.13; Q3: 1.01, 95% CI: 0.87, 1.18; Q4: 0.90, 95% CI: 0.76, 1.05; Q5: 0.84, 95% CI: 0.70, 1.01; 1- point increase: 0.95, 95% CI: 0.91, 0.99; HPFS; Q1: REF; Q2: 1.07, 95% CI: 0.93, 1.24; Q3: 0.98, 95% CI: 0.85, 1.13; Q4: 0.97, 95% CI: 0.83, 1.12; Q5: 0.92, 95% CI: 0.78, 1.08; 1- point increase: 0.96, 95% CI: 0.93, 0.99; NHS II; Q1: REF; Q2: 0.92, 95% CI: 0.69, 1.24; Q3: 1.01, 95% CI: 0.75, 1.37; Q4: 0.91, 95% CI: 0.65, 1.27; Q5: 0.79, 95% CI: 0.52, 1.20; 1- point increase: 0.93, 95% CI: 0.85, 1.01; PDQS vs. total IHD, RR, 95% CI; NHS I; Q1: REF; Q2: 0.88, 95% CI: 0.79, 0.98; Q3: 0.89, 95% CI: 0.79, 0.99; Q4: 0.77, 95% CI: 0.68, 0.87; Q5: 0.70, 95% CI: 0.61, 0.79; Point increase: 0.87, 95% CI: 0.83, 0.91; HPFS; Q1: REF; Q2: 0.96, 95% CI: 0.87, 1.06; Q3: 0.93, 95% CI: 0.84, 1.03; Q4: 0.91, 95% CI: 0.82, 1.01; Q5: 0.79, 95% CI: 0.70, 0.88; Point increase: 0.90, 95% CI: 0.87, 0.94; NHS II; Q1: REF; Q2: 0.95, 95% CI: 0.74, 1.21; Q3: 0.80, 95% CI: 0.61, 1.04; Q4: 0.83, 95% CI: 0.63, 1.09; Q5: 0.63, 95% CI: 0.46, 0.86; Point increase: 0.85, 95% CI: 0.76, 0.94; Summary: Inverse: PDQS & Ischemic heart disease; Inverse: MDDW (NHS, HPFS) & Ischemic heart disease; Null: FGI & Ischemic heart disease | - Did not account for: SEP (100% nurses, health professionals); - Dietary assessment: Multiple exposure assessment; - Outcome measurement: Medical record abstraction + National Death Index; - Generalizability may be an issue since most participants are White and are health professionals; - Funding: NIH
George, 2014^45^; United States; WHI; Analytic N=63805; Participant characteristics:; - [underlined: Race and/or Ethnicity]:; 73-91% NHW; 4-14% Black; 2-7% Hispanic; 3-6% Other; - [underlined: SEP]: College graduate: 29-57%; - [underlined: Selection:] Excluded those with incomplete/implausible diet data (<600 or >5000 kcals), prior CVD or cancer, missing information on diabetes status | - DP Age(s): 50 to 79 y, at baseline; Mean age (stratified by DP): ~62-~64 y; - DP(s) examined: Healthy Eating Index (HEI-2010) [Guenther 2013]; - Alternative HEI (AHEI)-2010 [Chiuve 2012]; - Alternate Med Diet Score (aMED) [Fung 2005]; - DASH Score [Fung 2008]; - DP Components: HEI: Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; Fatty Acids (PUFA+MUFA/SFA). Negative: Refined Grains; Added Sugars in “Empty Calories”; Solid Fats in “Empty Calories”; Sodium; - AHEI-2010: Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol; - aMED: Positive: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA/SFA. Negative: Red and Processed Meat. Neutral: Alcohol; - DASH: Positive: Vegetables (not potatoes and legumes); Nuts, seeds. legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Sodium; - DP Method(s): Index; Comparisons: Categorical, quintiles | Follow-Up Duration: 12.9 y; HEI vs. CVD deaths, HR, 95% CI; Q1: REF; Q2: 1.07, 95% CI: 0.91, 1.25; Q3: 0.99, 95% CI: 0.84, 1.17; Q4: 0.88, 95% CI: 0.75, 1.05; Q5: 0.78, 95% CI: 0.65, 0.93; Q5:Q1 p=0.0006; HEI vs. CVD deaths, HR, 95% CI (stratified by BMI) BMI<25: 0.74, 95% CI: 0.56, 0.98; p-value: 0.038 BMI 25-29.9: 0.72, 95% CI: 0.52, 1.00, p-value: 0.047; BMI >=30: 0.87, 95% CI: 0.61, 1.23, p-value: 0.420 P-interaction: 0.665; AHEI vs. CVD deaths, HR, 95% CI; Q1: REF; Q2: 0.99, 95% CI: 0.85, 1.16; Q3: 0.94, 95% CI: 0.80, 1.10; Q4: 0.77, 95% CI: 0.65, 0.91; Q5: 0.81, 95% CI: 0.68, 0.96; Q5:Q1 p=0.017; AHEI vs. CVD deaths, HR, 95% CI (stratified by BMI) BMI<25: 0.82, 95% CI: 0.62, 1.09; p-value: 0.172 BMI 25-29.9: 0.70, 95% CI: 0.51, 0.96, p-value: 0.025 BMI >=30: 0.93, 95% CI: 0.66, 1.30, p-value: 0.661 P-interaction: 0.674; aMED vs. CVD deaths, HR, 95% CI; Q1: REF; Q2: 0.86, 95% CI: 0.73, 1.01; Q3: 0.82, 95% CI: 0.70, 0.97; Q4: 0.87, 95% CI: 0.74, 1.03; Q5: 0.79, 95% CI: 0.67, 0.94; Q5:Q1 p=0.006; aMED vs. CVD deaths, HR, 95% CI (stratified by BMI) BMI<25: 0.81, 95% CI: 0.62, 1.07; p-value: 0.138; BMI 25-29.9: 0.60, 95% CI: 0.44, 0.81, p-value: 0.0008; BMI >=30: 0.99, 95% CI: 0.73, 1.36, p-value: 0.972 P-interaction: 0.836; DASH vs. CVD deaths, HR, 95% CI; Q1: REF; Q2: 0.91, 95% CI: 0.77, 1.08; Q3: 0.89, 95% CI: 0.77, 1.04; Q4: 0.93, 95% CI: 0.79, 1.11; Q5: 0.76, 95% CI: 0.65, 0.90; Q5:Q1 p=0.002; DASH vs. CVD deaths, HR, 95% CI (stratified by BMI) BMI<25: 0.71, 95% CI: 0.54, 0.93; p-value: 0.013; BMI 25-29.9: 0.81, 95% CI: 0.60, 1.08, p-value: 0.148; BMI >=30: 0.75, 95% CI: 0.54, 1.04, p-value: 0.082; P-interaction: 0.001; Summary: Inverse: HEI, AHEI, aMED, or DASH & CVD mortality; Inverse: HEI (BMI<25, BMI >25-29.9) & CVD mortality; Inverse: AHEI (BMI 25-29.9 ) & CVD mortality; Inverse: aMED (BMI 25-29.9) & CVD mortality; Inverse: DASH (BMI<25) & CVD mortality; NS/Null: HEI (BMI≥30), AHEI (BMI<25, ≥30), aMED (BMI<25, ≥30), DASH (BMI 25-29.9, BMI≥30)& CVDmortality | - Did not account for: None (all); - Dietary assessment: Single time point measurement of exposure; - Outcome measurement: National Death Index + adjudication; - Single time point measure of exposure; For SEP, only marital status was accounted for; - Funding: NCI; NHLBI
George, 2021^46^; United States; WHI-OS; Analytic N=59,388; Participant characteristics:; - [underlined: Race and/or Ethnicity]: 85%; NHW; 7% NHB; 4% Hispanic; 5% Other; - [underlined: SEP]: Graduate or higher level education (Stratified by DP): 31-54%; - Family income <50k (stratified by DP): 48-60%; - [underlined: Selection:] Excluded those with CVD, Cx, DM or missing DM data, missing/implausible diet data, missing BMI or smoking; - Mean BMI: 26.8 kg/m2 | - DP Age(s): 50 to 79 y at baseline; Mean age: 63 y; - DP(s) examined: Healthy Eating Index (HEI-2015) [Krebs-Smith 2018]; - DP Components: Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; PUFA+MUFA/SFA. Negative: Refined Grains; Added Sugars; SFA; Sodium; - DP Method(s): Index; Comparisons: Categorical, quintiles | Follow-Up Duration: 18.2 y; CVD mortality; HEI-2015 vs. CVD mortality, HR, 95% CI; Q1: REF; Q2: 1.02, 95% CI: 0.90, 1.17; Q3: 0.99, 95% CI: 0.87, 1.14; Q4: 0.85, 95% CI: 0.73, 0.97; Q5: 0.94, 95% CI: 0.82, 1.08; Sub-group analysis, limiting to women without known hypertension; HR: 0.86, 95% CI: 0.71, 1.04; Summary: NS/Null: HEI-2015 & CVD Death | - Did not account for: None (all); - Dietary assessment: Single time point measurement of exposure; - Outcome measurement: National Death Index + adjudication; - Data in this study are from extended f/u (median 18.2 y) than previous publication (median 12.9y); - Additional analyses excluding for LFU <2 y, by smoking, or income did not considerbly change results; - Diet assessed using FFQ once at baseline only; - Funding: NIH
Glenn, 2021^47^; United States; WHI; Analytic N=104,894; Participant characteristics:; - [underlined: Race and/or Ethnicity]:; 83% NHW; 8% NHB; 5% Hispanic; 3% Asian; - [underlined: SEP]: College and above: 60-78%; - [underlined: Selection:] Excluded those with Hx CVD, missing/implausible data; - 100% Postmenopausal women; - Mean BMI: ~28 kg/m2; - 29.6% Hypertension | - DP Age(s): 50 to 79 y at baseline; Mean age: 63 y; - DP(s) examined: Portfolio Diet Score [Glenn, 2021]; - DP Components: Portfolio Diet Score: Positive: Plant protein (Soy beverage; green peas; refried beans; all other beans; tofu and textured vegetable products; bean soups); Viscous fiber (Oranges, grapefruit & tangerines, apples & pears, strawberries, okra, oats); (5) cooked cereals & grits); Nuts (Peanut butter, peanuts, other nuts and seeds); Phytosterols; MUFAs (Olive or canola oil; avocado and guacamole); Negative: Saturated fat (High fat dairy; eggs; chicken/turkey with skin; red and processed meats; organ meats; gravy; butter); - DP Method(s): Index; Comparisons: Categorical, quartiles | Follow-Up Duration: 15.3 y; PDS vs. Total CVD (fatal + non-fatal), HR, 95% CI; Q1: REF; Q2: 0.97, 95% CI: 0.92, 1.02; Q3: 0.91, 95% CI: 0.86, 0.96; Q4: 0.89, 95% CI: 0.83, 0.94; p-trend<0.001; Q1 vs. Q4: 0.89, 95% CI: 0.83, 0.94; PDS vs. CHD (fatal + non-fatal), HR, 95% CI; Q1: REF; Q2: 0.92, 95% CI: 0.85, 0.99; Q3: 0.85, 95% CI: 0.78, 0.93; Q4: 0.86, 95% CI: 0.78, 0.95; p-trend<0.001 Q1 vs. Q4: 0.86, 95% CI: 0.78, 0.95; PDS vs. Stroke (fatal + non-fatal), HR, 95% CI; Q1: REF; Q2: 1.03, 95% CI: 0.95, 1.13; Q3: 0.97, 95% CI: 0.88, 1.07; Q4: 0.97, 95% CI: 0.87, 1.08; p-trend: 0.500; Q1 vs. Q4: 0.97, 95% CI: 0.87, 1.08; PDS vs.HF (fatal + non-fatal), HR, 95% CI; Q1: REF; Q2: 0.97, 95% CI: 0.85, 1.11; Q3: 0.86, 95% CI: 0.75, 0.99; Q4: 0.83, 95% CI: 0.71, 0.99; p-trend: 0.010; Q1 vs. Q4: 0.83, 95% CI: 0.71, 0.99; PDS (Q1 vs. Q4) vs. total CVD, HR, 95% CI; Age; <50-59: 0.82, 95% CI: 0.70, 0.96; 60-69: 0.96, 95% CI: 0.88, 1.05; 70+: 0.88, 95% CI: 0.79, 0.97; P-interaction: 0.36; BMI; <25: 0.88, 95% CI: 0.79, 0.99; 25 to <30: 0.92, 95% CI: 0.82, 0.99; ≥30: 0.85, 95% CI: 0.76, 0.94; P-interaction: 0.07; Ethnicity; White: 0.87, 95% CI: 0.82, 0.93; African American: 0.92, 95% CI: 0.73, 1.16; Hispanic: 0.92, 95% CI: 0.63, 1.36; Asian: 1.53, 95% CI: 0.94, 2.49; P-interaction: 0.11; PDS (Q1 vs. Q4) vs. CHD, HR, 95% CI; Age; <50-59: 0.77, 95% CI: 0.59, 0.98; 60-69: 0.88, 95% CI: 0.76, 1.01; 70+: 0.94, 95% CI: 0.81, 1.09; P-interaction: 0.05; BMI; <25: 0.84, 95% CI: 0.71, 1.00; 25 to <30: 0.84, 95% CI: 0.72, 0.99; ≥30: 0.89, 95% CI: 0.76, 1.05; P-interaction: 0.26; Ethnicity; White: 0.88, 95% CI: 0.79, 0.97; African American: 0.68, 95% CI: 0.46, 0.98; Hispanic: 0.81, 95% CI: 0.41, 1.60; Asian: 1.70, 95% CI: 0.77, 3.76; P-interaction: 0.61; PDS (Q1 vs. Q4) vs. Stroke, HR, 95% CI; Age; <50-59: 1.09, 95% CI: 0.81, 1.47; 60-69: 1.11, 95% CI: 0.94, 1.30; 70+: 0.86, 95% CI: 0.72, 1.03; P-interaction: 0.38; BMI; <25: 0.98, 95% CI: 0.81, 1.19; 25 to <30: 1.07, 95% CI: 0.89, 1.28; ≥30: 0.88, 95% CI: 0.72, 1.07; P-interaction: 0.65; Ethnicity; White: 0.93, 95% CI: 0.83, 1.05; African American: 1.17, 95% CI: 0.81, 1.68; Hispanic: 1.07, 95% CI: 0.55, 2.09; Asian: 1.35, 95% CI: 0.68, 2.71; P-interaction: 0.11; PDS (Q1 vs. Q4) vs. HF, HR, 95% CI; Age; <50-59: 0.87, 95% CI: 54, 1.42; 60-69: 0.96, 95% CI: 0.73, 1.13; 70+: 0.77, 95% CI: 0.60, 0.99; P-interaction: 0.97; BMI; <25: 0.91, 95% CI: 0.66, 1.24; 25 to <30: 1.03, 95% CI: 0.75, 1.43; ≥30: 0.65, 95% CI: 0.50, 0.84; P-interaction: 0.12; Ethnicity; White: 0.82, 95% CI: 0.69, 0.99; African American: 0.93, 95% CI: 0.51, 1.67; Hispanic: 0.84, 95% CI: 0.28, 2.54; Asian: 1.41, 95% CI: 0.26, 7.54; P-interaction: 0.99; Summary: Inverse: Portfiolio Diet Score & Total CVD; Portfolio diet score & total CVD in <50-59, 70+; all BMI; White; Inverse: Portfiolio Diet Score & CHD; Portfolio diet score & CHD in <50-59 y, BMI (25 to <30 kg/m2), White and African Americans; Inverse: Portfiolio Diet Score & HF; Portfolio diet score & HF in 70+, BMI > 30 kg/m2, White; Null: Portfolio Diet Score & Stroke;; Null: Portfolio diet score & total CVD in 60-69 y old, African Americans, Hispanic and Asians;; Null: Portfolio diet score & CHD in 60-69, 70+ y old, BMI (<25 and ≥30 kg/m2), Hispanic and Asians;; Null: Portfolio diet score & HF in <50-59, 60-69 y old; BMi <25, 25-<30 kg/m2, African Americans, Hispanic and Asians | - Did not account for: None (all); - Dietary assessment: Multiple exposure assessment; - Outcome measurement: Composite of fatal and non-fatal; Medical record abstraction + adjudication +Death certificates; - All outcomes were composite of fatal and non-fatal. Participants that were excluded (vs. included) were more likely to be Blacks (19.0% vs, 8.2%) or Hispanics (10.2% vs. 4%) when compared to Whites (65.5% vs. 84.0%); Similarly, participants excluded were less likely to have college degree (55.9% vs. 68.5%). However, statistical significance is not provided.; - Funding: NIH, DHHS
Goyal, 2021^48^; United States; REGARDS; Analytic N=18,856; Participant characteristics:; - [underlined: Race and/or Ethnicity]: 32.5% Black; - [underlined: SEP]: <High school: 8.8%;; - Annual income <$20k: 16.5%; - No health insurance: 6.3%; - [underlined: Selection:] Excluded participants with a history of stroke, incomplete/missing data, implausible energy intake; - All at high-risk of stroke, without suspected baseline HF;; - Female: 55.9%; - Mean BMI: 29 kg/m2; - Hypertension: 54.9%; - Dyslipidemia: 58% | - DP Age(s): ≥45 y at baseline; Mean age: 64 y; - DP(s) examined: DASH Score [Fung 2008]; - DP Components: DASH: Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Sodium; - DP Method(s): Index; Comparisons: Categorical, quartiles, deciles | Follow-Up Duration: 10.1 y; DASH vs. HF (fatal + non-fatal), HR, 95% CI; Q1: REF; Q2: 0.69, 95% CI: 0.56, 0.85; Q3: 0.71, 95% CI: 0.58, 0.87; Q4: 0.73, 95% CI: 0.58, 0.92; DASH vs. HF (fatal + non-fatal), HR, 95% CI; Age <65; Q1: REF; Q2: 0.56, 95% CI: 0.39, 0.81; Q3: 0.54, 95% CI: 0.37, 0.79; Q4: 0.48, 95% CI: 0.30, 0.78; DASH vs. HF (fatal + non-fatal), HR, 95% CI; Age 65-74; Q1: REF; Q2: 0.79, 95% CI: 0.58, 1.08; Q3: 0.57, 95% CI: 0.42, 0.79; Q4: 0.65, 95% CI: 0.46, 0.92; DASH vs. HF (fatal + non-fatal), HR, 95% CI; Age≥75; Q1: REF; Q2: 0.81, 95% CI: 0.54, 1.24; Q3: 1.21, 95% CI: 0.83, 1.76; Q4: 1.12, 95% CI: 0.75, 1.66; DASH vs. HF (fatal +non-fatal), HR, 95% CI; D1: REF; D2: 0.79, 95% CI: 0.59, 1.05; D3: 0.63, 95% CI: 0.47, 0.83; D4: 0.57, 95% CI: 0.41, 0.79; D5: 0.66, 95% CI: 0.48, 0.92; D6: 0.59, 95% CI: 0.42, 0.84; D7: 0.61, 95% CI: 0.43 ,0.86; D8: 0.62, 95% CI: 0.46, 0.84; D9: 0.61, 95% CI: 0.44, 0.86; D10: 0.69, 95% CI: 0.49, 0.98; DASH vs. HF reduction ejection fraction, HR, 95% CI; Q1: REF; Q2: 0.72, 95% CI: 0.53, 0.98; Q3: 0.63, 95% CI: 0.47, 0.86; Q4: 0.69, 95% CI: 0.49, 0.96; DASH vs. HF with preserved ejection fraction, HR, 95% CI; Q1: REF; Q2: 0.75, HR: 0.51, 1.1; Q3: 1.00, HR: 0.71, 1.4; Q4: 1.02, HR: 0.70, 1.49; Summary: Inverse: DASH Score & HF (quartiles, deciles); Inverse: DASH score & HF (<65, 65-74 (Q3, Q4)); Inverse: DASH score & HFrEF; NS/Null: DASH score & heart failure in ages ≥75;; NS/Null: DASH score & HFpEF | - Did not account for: None (all); - Dietary assessment: Single time point measurement of exposure; - Outcome measurement: Composite of fatal and non-fatal; Medical record abstraction + adjudication +Death certificates; - Outcome is composite of fatal and non-fatal; Statistical significant difference between those who has diet data and those who did not and hence were not included. Dietary data measured at single time-point using FFQ; Unsure if FFQ is validated; - Funding: NIH
Gu, 2022^49^; United States; HPFS; Analytic N=44,525; Participant characteristics:; - [underlined: Race and/or Ethnicity]: 91% White participants; - [underlined: SEP]: 100% health professionals (male veterinarians, dentists, pharmacists, optometrists, osteopath physicians, and podiatrists); - [underlined: Selection:] Excluded participants with a history of heart failure, MI, stroke, coronary artery bypass grafting, cancer, implausible energy intake, missing age, missing AHEI or PDQS | - DP Age(s): 40 to 75 y at baseline; Mean age at baseline: 52.7 y; - DP(s) examined: Alternative HEI (AHEI)-2010 [Chiuve 2012]; Prime Diet Quality Score (PDQS) [Gu, 2022 ]; - DP Components: AHEI-2010: Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol; - PDQS: Positive: Dark leafy green vegetables, cruciferous vegetables, carrots, other vegetables, whole citrus fruits, other whole fruits, legumes, nuts, poultry, fish, eggs, whole grains, and liquid vegetable oils; Negative: Red meat, potatoes, processed meat, whole-milk dairy products, refined grains and baked goods, sugarsweetened beverages, fried foods obtained away from home, and desserts and ice cream; - DP Method(s): Index; Comparisons: Continuous (per SD), Categorical: quintiles of AHEI, PDQS | Follow-Up Duration: 22 y; AHEI vs. HF, HR, 95% CI; Per SD: 0.96, 95% CI: 0.89, 1.04; Q1: REF; Q2: 0.98, 95% CI: 0.78, 1.24; Q3: 0.93, 95% CI: 0.74, 1.18; Q4: 1.05, 95% CI: 0.84, 1.32; Q5: 0.90, 95% CI: 0.71, 1.15; p-linear: 0.57; p-quadratic: 0.72; AHEI vs. HFpEF, HR, 95% CI; Per SD: 1.00, 95% CI: 0.86, 1.18; Q1: REF; Q2: 1.11, 95% CI: 0.65, 1.89; Q3: 1.15, 95% CI: 0.68, 1.95; Q4: 1.43, 95% CI: 0.86, 2.38; Q5: 1.05, 95% CI: 0.62, 1.79; p-linear: 0.65; p-quadratic: 0.58; AHEI vs. HFrEF, HR, 95% CI; Per SD: 0.81, 95% CI: 0.69, 0.96; Q1: REF; Q2: 0.74, 95% CI: 0.48, 1.15; Q3: 0.59, 95% CI: 0.37, 0.93; Q4: 0.50, 95% CI: 0.31, 0.81; Q5: 0.61, 95% CI: 0.38, 0.97; p-linear: 0.02; p-quadratic: 0.34; PDQS vs. HF, HR, 95% CI; Per SD: 0.98, 95% CI: 0.91, 1.06; Q1: REF; Q2: 1.09, 95% CI: 0.86, 1.39; Q3: 0.99, 95% CI: 0.78, 1.26; Q4: 1.02, 95% CI: 0.80, 1.29; Q5: 1.01, 95% CI: 0.79, 1.29; p-linear: 0.82; p-quadratic: 0.97; PDQS vs. HFpEF, HR, 95% CI; Per SD: 1.05, 95% CI: 0.91, 1.22; Q1: REF; Q2: 1.58, 95% CI: 0.89, 2.81; Q3: 1.56, 95% CI: 0.88, 2.76; Q4: 1.66, 95% CI: 0.95, 2.90; Q5: 1.44, 95% CI: 0.81, 2.55 p-linear: 0.31 p-quadratic: 0.06; PDQS vs. HFrEF, HR, 95% CI; Per SD: 0.80, 95% CI: 0.68, 0.95; Q1: REF; Q2: 0.80, 95% CI: 0.51, 1.25; Q3: 0.55, 95% CI: 0.34, 0.89; Q4: 0.60, 95% CI: 0.38, 0.93; Q5: 0.64, 95% CI: 0.40, 1.00 p-linear: 0.03 p-quadratic: 0.03; Summary: NS/Null: AHEI-2010, PDQS & HF, HFpEF; Inverse: AHEI-2010, PDQS & HFrEF | - Did not account for: SEP; - Dietary assessment: Multiple exposure assessment; - Outcome measurement: Medical record abstraction + adjudication +Death certificates; - Diet assessed every 4y via FFQ; DP based on cumulative avg. from 6 FFQ; As noted in the limitation, authors did not exclude participants that developed intermediateoutcomes such as diabetes, MI, hypertension, hypercholesterolemia, CABG. EF data not available for all participants and some analysis had little power. Participants with missing EF tended to be less health conscious.; - Funding: NIH/NCI, NHLBI
Guasch-Ferré, 2022^50^; United States; NHS, HPFS; Analytic N=96,344; Participant characteristics:; - [underlined: Race and/or Ethnicity]: >95% Whites; - [underlined: SEP]: 100% health professionals, nurses; - [underlined: Selection:] Excluded participants who reported CVD at baseline, with implausible energy intakes; BMI <18.5 kg/m2 at baseline; or with missing information on BMI, physical activity, alcohol intake, sleep duration, or smoking; - Baseline high BP: ~16% in NHS; ~25% in HPFS | - DP Age(s): 30 to 55 y at baseline, NHS; Mean age at baseline: 46.3 y; - 40 to 75 y at baseline, HPFS; Mean age at baseline: 55 y; - DP(s) examined: Alternative HEI (AHEI)-2010 [Chiuve 2012]; - DP Components: AHEI-2010: Positive: Vegetables (not potatoes, French fries); Fruit; Nuts and Soy Protein; Cereal Fiber; White: Red Meat Ratio; PUFA:SFA; Multi-Vitamin Use. Negative: Trans-UFA. Neutral: Alcohol; - DP Method(s): Index; Comparisons: Categorical: Quintiles of AHEI | Follow-Up Duration: 30 y; AHEI vs. CVD, HR, 95% CI; Q1: REF; Q2: 0.91, 95% CI: 0.86, 0.96; Q3: 0.91, 95% CI: 0.86, 0.96; Q4: 0.80, 95% CI: 0.75, 0.85; Q5: 0.75, 95% CI: 0.70, 0.79; AHEI vs. CHD, HR, 95% CI; Q1: REF; Q2: 0.89, 95% CI: 0.83, 0.96; Q3: 0.91, 95% CI: 0.85, 0.98; Q4: 0.79, 95% CI: 0.74, 0.85; Q5: 0.74, 95% CI: 0.69, 0.79; AHEI vs. Stroke, HR, 95% CI; Q1: REF; Q2: 0.95, 95% CI: 0.87, 1.04; Q3: 0.92, 95% CI: 0.84, 1.01; Q4: 0.81, 95% CI: 0.73, 0.89; Q5: 0.77, 95% CI: 0.69, 0.84; Summary: Inverse: AHEI (quintile) & CVD and CHD; Inverse: AHEI (Q4, Q5 vs. Q1) & stroke; NS/Null: AHEI (Q2, Q3 vs. Q1) & Stroke | - Did not account for: Physical activity, Anthropometry, Smoking, (part of a composite score that included PA, anthropometry, smoking), SEP, Other: Total E; - Dietary assessment: Multiple exposure assessment; - Outcome measurement: Medical record abstraction + National Death Index; - All participants are health professionals and predominantly white, so the findings may not be generalizable. Many of the KC were not adjusted for because they were independent variables that were accounted for. Physical activity, smoking and anthropometry were separate exposures in the study, which along with diet was used to create a composite.; - Funding: NIH/NCI, NHLBI, NIDDK
Harmon, 2015^51^; United States; Multiethnic Cohort Study; Analytic N= 156,804; Participant characteristics:; - [underlined: Race and/or Ethnicity]:; ~21% White; ~22% African American; ~20% Native Hawaiian; ~19% Japanese American; ~19% Latino; - [underlined: SEP]: Education, % graduated from college (stratified by DP); - Men: 22.0-38.8%; - Women: 18-31.4%; - [underlined: Selection:] Excluded participants with a history of cancer, heart attack, or stroke, missing valid dietary assessment; - Mean BMI: ~26 kg/m2 | - DP Age(s): 45 to 75 y at baseline; Mean age for men (stratified by DP): ~57-61 y; Mean age for women (stratified by DP): ~57 - 62 y; - DP(s) examined: Healthy Eating Index (HEI-2010) [Guenther 2013]; Alternative HEI (AHEI)-2010 [Chiuve 2012]; Alternate Med Diet Score (aMED) [Fung 2005]; DASH Score [Fung 2008]; - DP Components: HEI-2010: Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; Fatty Acids. Negative: Refined Grains; Added Sugars in “Empty Calories”; Solid Fats in “Empty Calories”; Sodium; - AHEI-2010: Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol; - aMED: Positive: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA/SFA. Negative: Red and Processed Meat. Neutral: Alcohol; - DASH: Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Sodium; - DP Method(s): Index; Comparisons: Categorical, quintiles | Follow-Up Duration: 13-18 y; HEI-2010 vs. CVD mortality, HR, 95% CI (Men); Q1: REF; Q2: 0.87, 95% CI: 0.80, 0.94; Q3: 0.83, 95% CI: 0.77, 0.90; Q4: 0.84, 95% CI: 0.77, 0.91; Q5: 0.74, 95% CI: 0.69, 0.81; aHEI-2010 vs. CVD mortality, HR, 95% CI (Men); Q1: REF; Q2: 0.96, 95% CI: 0.80, 1.04; Q3: 0.89, 95% CI: 0.77, 0.96; Q4: 0.92, 95% CI: 0.77, 0.99; Q5: 0.79, 95% CI: 0.72, 0.86; aMED vs. CVD mortality, HR, 95% CI (Men); Q1: REF; Q2: 0.97, 95% CI: 0.89, 1.04; Q3: 0.87, 95% CI: 0.81, 0.95; Q4: 0.84, 95% CI: 0.77, 0.91; Q5: 0.79, 95% CI: 0.72, 0.86; DASH vs. CVD mortality, HR, 95% CI (Men); Q1: REF; Q2: 0.95, 95% CI: 0.88, 1.02; Q3: 0.94, 95% CI: 0.87, 1.02; Q4: 0.86, 95% CI: 0.79, 0.93; Q5: 0.83, 95% CI: 0.76, 0.91; HEI-2010 vs. CVD mortality, HR, 95% CI (Women); Q1: REF; Q2: 0.91, 95% CI: 0.84, 1.00; Q3: 0.92, 95% CI: 0.85, 1.00; Q4: 0.79, 95% CI: 0.73, 0.87; Q5: 0.77, 95% CI: 0.71, 0.84; aHEI-2010 vs. CVD mortality, HR, 95% CI (Women); Q1: REF; Q2: 0.90, 95% CI: 0.83, 0.98; Q3: 0.87, 95% CI: 0.80, 0.95; Q4: 0.82, 95% CI: 0.75, 0.90; Q5: 0.76, 95% CI: 0.69, 0.83; aMED vs. CVD mortality, HR, 95% CI (Women); Q1: REF; Q2: 0.91, 95% CI: 0.83, 0.99; Q3: 0.85, 95% CI: 0.78, 0.93; Q4: 0.82, 95% CI: 0.75, 0.90; Q5: 0.81, 95% CI: 0.69, 0.89; DASH vs. CVD mortality, HR, 95% CI (Women); Q1: REF; Q2: 0.91, 95% CI: 0.84, 0.98; Q3: 0.86, 95% CI: 0.79, 0.94; Q4: 0.78, 95% CI: 0.72, 0.85; Q5: 0.78, 95% CI: 0.71, 0.85; HEI-2010 vs. CVD mortality, HR (Q1 vs. Q5), 95% CI (Men); White: 0.63, 95% CI: 0.53, 0.75; African American: 0.70, 95% CI: 0.59, 0.83; Native Hawaiian: 0.83, 95% CI: 0.63, 1.08; Japanese American: 0.69, 95% CI: 0.59, 0.81; Latino: 1.01, 95% CI: 0.84, 1.21; HEI-2010 vs. CVD mortality, HR (Q1 vs. Q5), 95% CI (Women); White: 0.65, 95% CI: 0.54, 0.80; African American: 0.72, 95% CI: 0.61, 0.84; Native Hawaiian: 0.88, 95% CI: 0.64, 1.20; Japanese American: 0.85, 95% CI: 0.70, 1.04; Latino: 0.96, 95% CI: 0.77, 1.19; AHEI-2010 vs. CVD mortality, HR (Q1 vs. Q5), 95% CI (Men); White: 0.68, 95% CI: 0.57, 0.81; African American: 0.75, 95% CI: 0.62, 0.90; Native Hawaiian: 1.09, 95% CI: 0.81, 1.45; Japanese American: 0.79, 95% CI: 0.67, 0.93; Latino: 0.87, 95% CI: 0.72, 1.05; AHEI-2010 vs. CVD mortality, HR (Q1 vs. Q5), 95% CI (Women); White: 0.73, 95% CI: 0.60, 0.89; African American: 0.71, 95% CI: 0.61, 0.83; Native Hawaiian: 1.00, 95% CI: 0.72, 1.39; Japanese American: 0.61, 95% CI: 0.50, 0.74; Latino: 0.94, 95% CI: 0.74, 1.18; aMED vs. CVD mortality, HR (Q1 vs. Q5), 95% CI (Men); White: 0.70, 95% CI: 0.59, 0.84; African American: 0.75, 95% CI: 0.62, 0.90; Native Hawaiian: 0.82, 95% CI: 0.61, 1.09; Japanese American: 0.80, 95% CI: 0.68, 0.94; Latino: 0.90, 95% CI: 0.75, 1.08; aMED vs. CVD mortality, HR (Q1 vs. Q5), 95% CI (Women); White: 0.77, 95% CI: 0.62, 0.95; African American: 0.82, 95% CI: 0.70, 0.97; Native Hawaiian: 1.00, 95% CI: 0.72, 1.39; Japanese American: 0.72, 95% CI: 0.59, 0.87; Latino: 0.89, 95% CI: 0.71, 1.11; DASH vs. CVD mortality, HR (Q1 vs. Q5), 95% CI (Men); White: 0.71, 95% CI: 0.58, 0.86; African American: 0.73, 95% CI: 0.60, 0.89; Native Hawaiian: 0.97, 95% CI: 0.71, 1.32; Japanese American: 0.81, 95% CI: 0.69, 0.95; Latino: 1.12, 95% CI: 0.93, 1.36; DASH vs. CVD mortality, HR (Q1 vs. Q5), 95% CI (Women); White: 0.63, 95% CI: 0.51, 0.78; African American: 0.65, 95% CI: 0.54, 0.77; Native Hawaiian: 1.12, 95% CI: 0.80, 1.56; Japanese American: 0.87, 95% CI: 0.72, 1.05; Latino: 0.91, 95% CI: 0.73, 1.14 HEI-2010 vs. CVD mortality, HR, 95% CI (Men); Q1: REF; Q2: 0.87, 95% CI: 0.80, 0.94; Q3: 0.83, 95% CI: 0.77, 0.90; Q4: 0.84, 95% CI: 0.77, 0.91; Q5: 0.74, 95% CI: 0.69, 0.81; aHEI-2010 vs. CVD mortality, HR, 95% CI (Men); Q1: REF; Q2: 0.96, 95% CI: 0.80, 1.04; Q3: 0.89, 95% CI: 0.77, 0.96; Q4: 0.92, 95% CI: 0.77, 0.99; Q5: 0.79, 95% CI: 0.72, 0.86; aMED vs. CVD mortality, HR, 95% CI (Men); Q1: REF; Q2: 0.97, 95% CI: 0.89, 1.04; Q3: 0.87, 95% CI: 0.81, 0.95; Q4: 0.84, 95% CI: 0.77, 0.91; Q5: 0.79, 95% CI: 0.72, 0.86; DASH vs. CVD mortality, HR, 95% CI (Men); Q1: REF; Q2: 0.95, 95% CI: 0.88, 1.02; Q3: 0.94, 95% CI: 0.87, 1.02; Q4: 0.86, 95% CI: 0.79, 0.93; Q5: 0.83, 95% CI: 0.76, 0.91; HEI-2010 vs. CVD mortality, HR, 95% CI (Women); Q1: REF; Q2: 0.91, 95% CI: 0.84, 1.00; Q3: 0.92, 95% CI: 0.85, 1.00; Q4: 0.79, 95% CI: 0.73, 0.87; Q5: 0.77, 95% CI: 0.71, 0.84; aHEI-2010 vs. CVD mortality, HR, 95% CI (Women); Q1: REF; Q2: 0.90, 95% CI: 0.83, 0.98; Q3: 0.87, 95% CI: 0.80, 0.95; Q4: 0.82, 95% CI: 0.75, 0.90; Q5: 0.76, 95% CI: 0.69, 0.83; aMED vs. CVD mortality, HR, 95% CI (Women); Q1: REF; Q2: 0.91, 95% CI: 0.83, 0.99; Q3: 0.85, 95% CI: 0.78, 0.93; Q4: 0.82, 95% CI: 0.75, 0.90; Q5: 0.81, 95% CI: 0.69, 0.89; DASH vs. CVD mortality, HR, 95% CI (Women); Q1: REF; Q2: 0.91, 95% CI: 0.84, 0.98; Q3: 0.86, 95% CI: 0.79, 0.94; Q4: 0.78, 95% CI: 0.72, 0.85; Q5: 0.78, 95% CI: 0.71, 0.85; HEI-2010 vs. CVD mortality, HR (Q1 vs. Q5), 95% CI (Men); White: 0.63, 95% CI: 0.53, 0.75; African American: 0.70, 95% CI: 0.59, 0.83; Native Hawaiian: 0.83, 95% CI: 0.63, 1.08; Japanese American: 0.69, 95% CI: 0.59, 0.81; Latino: 1.01, 95% CI: 0.84, 1.21; HEI-2010 vs. CVD mortality, HR (Q1 vs. Q5), 95% CI (Women); White: 0.65, 95% CI: 0.54, 0.80; African American: 0.72, 95% CI: 0.61, 0.84; Native Hawaiian: 0.88, 95% CI: 0.64, 1.20; Japanese American: 0.85, 95% CI: 0.70, 1.04; Latino: 0.96, 95% CI: 0.77, 1.19; AHEI-2010 vs. CVD mortality, HR (Q1 vs. Q5), 95% CI (Men); White: 0.68, 95% CI: 0.57, 0.81; African American: 0.75, 95% CI: 0.62, 0.90; Native Hawaiian: 1.09, 95% CI: 0.81, 1.45; Japanese American: 0.79, 95% CI: 0.67, 0.93; Latino: 0.87, 95% CI: 0.72, 1.05; AHEI-2010 vs. CVD mortality, HR (Q1 vs. Q5), 95% CI (Women); White: 0.73, 95% CI: 0.60, 0.89; African American: 0.71, 95% CI: 0.61, 0.83; Native Hawaiian: 1.00, 95% CI: 0.72, 1.39; Japanese American: 0.61, 95% CI: 0.50, 0.74; Latino: 0.94, 95% CI: 0.74, 1.18; aMED vs. CVD mortality, HR (Q1 vs. Q5), 95% CI (Men); White: 0.70, 95% CI: 0.59, 0.84; African American: 0.75, 95% CI: 0.62, 0.90; Native Hawaiian: 0.82, 95% CI: 0.61, 1.09; Japanese American: 0.80, 95% CI: 0.68, 0.94; Latino: 0.90, 95% CI: 0.75, 1.08; aMED vs. CVD mortality, HR (Q1 vs. Q5), 95% CI (Women); White: 0.77, 95% CI: 0.62, 0.95; African American: 0.82, 95% CI: 0.70, 0.97; Native Hawaiian: 1.00, 95% CI: 0.72, 1.39; Japanese American: 0.72, 95% CI: 0.59, 0.87; Latino: 0.89, 95% CI: 0.71, 1.11; DASH vs. CVD mortality, HR (Q1 vs. Q5), 95% CI (Men); White: 0.71, 95% CI: 0.58, 0.86; African American: 0.73, 95% CI: 0.60, 0.89; Native Hawaiian: 0.97, 95% CI: 0.71, 1.32; Japanese American: 0.81, 95% CI: 0.69, 0.95; Latino: 1.12, 95% CI: 0.93, 1.36; DASH vs. CVD mortality, HR (Q1 vs. Q5), 95% CI (Women); White: 0.63, 95% CI: 0.51, 0.78; African American: 0.65, 95% CI: 0.54, 0.77; Native Hawaiian: 1.12, 95% CI: 0.80, 1.56; Japanese American: 0.87, 95% CI: 0.72, 1.05; Latino: 0.91, 95% CI: 0.73, 1.14; Summary: Inverse: HEI-2010, AHEI-2010, aMED, or DASH & CVD-mortality (men and women); Inverse: HEI-2010, AHEI-2010, aMED, DASH & CVD mortality (White, African American men and women); Inverse: HEI-2010, AHEI-2010, aMED, DASH & CVD mortality (Japanese American men); AHEI-2010, aMED & CVD mortality (Japanese American women); Null: In Native Hawaiian, Latino men and women, HEI-2010, AHEI-2010, aMED, DASH & CVD mortality; Null: In Japanese American women HEI-2010, DASH & CVD mortality | - Did not account for: None (all); - Dietary assessment: Single time point measurement of exposure; - Outcome measurement: State registry + National Death Index; - Single point exposure assessment. Unclear if the authors accounted for multiple comparisons.; - Funding: NIH: NCI
Hu, 2019^52^; United States; ARIC Study; Analytic N=12,413; Participant characteristics:; - [underlined: Race and/or Ethnicity]:; White: ~78%; Black: ~22%; - [underlined: SEP]: Education:, ≥ college: 25-49%; - Income, <$24,000: 29-45%; - [underlined: Selection:] Excluded participants with a history of CHD, stroke, HF, missing covariates of interest, extreme energy intakes, incomplete FFQ. Only Black or White were included; Female: 56% | - DP Age(s): 45 to 64 y at baseline; Mean age: ~54 y; - DP(s) examined: Alternative HEI (AHEI)-2010 (Chiuve, 2012); Alternate Med Diet Score (aMED) (Fung, 2005); DASH Score (Fung, 2008); HEI-2015 (Krebs-Smith, 2018); - DP Components: AHEI-2010 Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: alcohol; aMED: Positive: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA/SFA. Negative: Red and Processed Meat. Neutral: alcohol; DASH: Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened beverages; Sodium; HEI-2015: Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; PUFA+MUFA/SFA. Negative: Refined Grains; Added Sugars; SFA; Sodium; - DP Method(s): Index; Comparisons: Categorical: quintiles | Follow-Up Duration: 24-25 y; AHEI-2010 vs. CVD mortality, HR, 95% CI; Q1: REF; Q2: 0.85, 95% CI: 0.74, 0.98; Q3: 0.83, 95% CI: 0.72, 0.96; Q4: 0.78, 95% CI: 0.67, 0.90; Q5: 0.66, 95% CI: 0.57, 0.77; p-trend <0.001; AHEI-2010 vs. CVD mortality, HR, 95% CI (White); Q1: REF; Q2: 0.85, 95% CI: 0.70, 1.02; Q3: 0.90, 95% CI: 0.75, 1.08; Q4: 0.83, 95% CI: 0.69, 1.00; Q5: 0.68, 95% CI: 0.56, 0.82; p-trend: <0.001; AHEI-2010 vs. CVD mortality, HR, 95% CI (Black); Q1: REF; Q2: 0.87, 95% CI: 0.69, 1.09; Q3: 0.74, 95% CI: 0.57, 0.96; Q4: 0.75, 95% CI: 0.58, 0.96; Q5: 0.68, 95% CI: 0.50, 0.92; p-trend: <0.001; aMED vs. CVD mortality, HR, 95% CI Q1: REF; Q2: 0.94, 95% CI: 0.81, 1.09; Q3: 0.86, 95% CI: 0.74, 0.99; Q4: 0.77, 95% CI: 0.66, 0.91; Q5: 0.66, 95% CI: 0.57, 0.77; p-trend <0.001; aMED vs. CVD mortality, HR, 95% CI (White); Q1: REF; Q2: 0.87, 95% CI: 0.72, 1.05; Q3: 0.92, 95% CI: 0.77, 1.11; Q4: 0.79, 95% CI: 0.65, 0.95; Q5: 0.65, 95% CI: 0.54, 0.78; p-trend: <0.001; aMED vs. CVD mortality, HR, 95% CI (Black); Q1: REF; Q2: 1.05, 95% CI: 0.81, 1.37; Q3: 0.74, 95% CI: 0.56, 0.97; Q4: 0.79, 95% CI: 0.60, 1.05; Q5: 0.72, 95% CI: 0.54, 0.95; p-trend: <0.001; DASH vs. CVD mortality, HR, 95% CI; Q1: REF; Q2: 0.90, 95% CI: 0.78, 1.03; Q3: 0.91, 95% CI: 0.79, 1.05; Q4: 0.91, 95% CI: 0.77, 1.07; Q5: 0.79, 95% CI: 0.68, 0.93; p-trend: 0.01; DASH vs. CVD mortality, HR, 95% CI (White); Q1: REF; Q2: 0.86, 95% CI: 0.72, 1.02; Q3: 0.85, 95% CI: 0.72, 1.02; Q4: 0.87, 95% CI: 0.71, 1.06; Q5: 0.78, 95% CI: 0.64, 0.94; p-trend: 0.01; DASH vs. CVD mortality, HR, 95% CI (Black); Q1: REF; Q2: 1.00, 95% CI: 0.79, 1.25; Q3: 1.06, 95% CI: 0.84, 1.33; Q4: 1.02, 95% CI: 0.74, 1.39; Q5: 0.87, 95% CI: 0.63, 1.20; p-trend: 0.7; HEI-2015 vs. CVD mortaity, HR, 95% CI; Q1: REF; Q2: 0.81, 95% CI: 0.71, 0.94; Q3: 0.75, 95% CI: 0.65, 0.87; Q4: 0.76, 95% CI: 0.65, 0.89; Q5: 0.68, 95% CI: 0.58, 0.80; p-trend <0.001; HEI-2015 vs. CVD mortality, HR, 95% CI (White); Q1: REF; Q2: 0.82, 95% CI: 0.69, 0.98; Q3: 0.76, 95% CI: 0.63, 0.91; Q4: 0.79, 95% CI: 0.66, 0.96; Q5: 0.66, 95% CI: 0.54, 0.81; p-trend: <0.001; HEI-2015 vs. CVD mortality, HR, 95% CI (Black); Q1: REF; Q2: 0.80, 95% CI: 0.62, 1.02; Q3: 0.74, 95% CI: 0.57, 0.95; Q4: 0.75, 95% CI: 0.58, 0.99; Q5: 0.76, 95% CI: 0.57, 1.02; p-trend: 0.04; AHEI-2010 vs. CVD, HR, 95% CI; Q1: REF; Q2: 0.96, 95% CI: 0.87, 1.05; Q3: 0.84, 95% CI: 0.77, 0.93; Q4: 0.84, 95% CI: 0.77, 0.92; Q5: 0.85, 95% CI: 0.77, 0.93; p-trend: <0.001; AHEI-2010 vs. CVD, HR, 95% CI (White); Q1: REF; Q2: 0.95, 95% CI: 0.86, 1.06; Q3: 0.84, 95% CI: 0.75, 0.94; Q4: 0.85, 95% CI: 0.76, 0.95; Q5: 0.84, 95% CI: 0.75, 0.93; p-trend: <0.001; AHEI-2010 vs. CVD, HR, 95% CI (Black); Q1: REF; Q2: 0.99, 95% CI: 0.84, 1.16; Q3: 0.88, 95% CI: 0.74, 1.05; Q4: 0.86, 95% CI: 0.72, 1.03; Q5: 0.96, 95% CI: 0.78, 1.18; p-trend: 0.3; aMED vs. CVD, HR, 95% CI; Q1: REF; Q2: 0.93, 95% CI: 0.84, 1.02; Q3: 0.94, 95% CI: 0.86, 1.03; Q4: 0.91, 95% CI: 0.82, 1.00; Q5: 0.84, 95% CI: 0.77, 0.93; P-trend: <0.001; aMED vs. CVD, HR, 95% CI (White); Q1: REF; Q2: 0.90, 95% CI: 0.81, 1.01; Q3: 0.93, 95% CI: 0.84, 1.04; Q4: 0.91, 95% CI: 0.82, 1.02; Q5: 0.83, 95% CI: 0.74, 0.92; p-trend: <0.001; aMED vs. CVD, HR, 95% CI (Black); Q1: REF; Q2: 1.03, 95% CI: 0.85, 1.26; Q3: 0.98, 95% CI: 0.71, 1.19; Q4: 0.94, 95% CI: 0.77, 1.15; Q5: 0.95, 95% CI: 0.78, 1.15; p-trend: 0.4; DASH vs. CVD, HR, 95% CI; Q1: REF; Q2: 0.97, 95% CI: 0.89, 1.05; Q3: 0.99, 95% CI: 0.91, 1.08; Q4: 1.00, 95% CI: 0.90, 1.11; Q5: 0.89, 95% CI: 0.81, 0.99; P-trend: 0.1; DASH vs. CVD, HR, 95% CI (White); Q1: REF; Q2: 0.93, 95% CI: 0.84, 1.03; Q3: 0.94, 95% CI: 0.85, 1.04; Q4: 0.96, 95% CI: 0.85, 1.08; Q5: 0.86, 95% CI: 0.77, 0.97; p-trend: 0.03; DASH vs. CVD, HR, 95% CI (Black); Q1: REF; Q2: 1.03, 95% CI: 0.88, 1.20; Q3: 1.12, 95% CI: 0.85, 1.32; Q4: 1.15, 95% CI: 0.93, 1.41; Q5: 1.01, 95% CI: 0.82, 1.25; p-trend: 0.3; HEI-2015 vs. CVD, HR, 95% CI; Q1: REF; Q2: 0.87, 95% CI: 0.79, 0.95; Q3: 0.89, 95% CI: 0.81, 0.98; Q4: 0.84, 95% CI: 0.77, 0.93; Q5: 0.84, 95% CI: 0.76, 0.93; p-trend <0.001; HEI-2015 vs. CVD, HR, 95% CI (White); Q1: REF; Q2: 0.89, 95% CI: 0.80, 0.99; Q3: 0.88, 95% CI: 0.79, 0.98; Q4: 0.82, 95% CI: 0.74, 0.92; Q5: 0.82, 95% CI: 0.73, 0.92; p-trend: <0.001; HEI-2015 vs. CVD, HR, 95% CI (Black); Q1: REF; Q2: 0.81, 95% CI: 0.68, 0.97; Q3: 0.90, 95% CI: 0.76, 1.08; Q4: 0.93, 95% CI: 0.77, 1.12; Q5: 0.94, 95% CI: 0.77, 1.15; p-trend: 0.9; Summary: Inverse: AHEI-2010, aMED, DASH, HEI-2015 scores & CVD-mortality; Inverse: AHEI-2010, aMED, HEI-2015 scores & incident CVD; Inverse: AHEI-2010, aMED, DASH, HEI-2015 scores & CVD-mortality, incident CVD in White; Inverse: HEI, aHEI, aMED and CVD mortality in Black; Null: DASH and incident CVD; Null: AHEI-2010, aMED, DASH, HEI-2015 scores & incident CVD in Black; Null: DASH and CVD mortality in Black | - Did not account for: Anthropometry; - Dietary assessment: Multiple exposure assessment; - Outcome measurement: Medical record abstraction + National Death Index; - Two time point measurement of diet using FFQ; Multiple comparisons not accounted for. Generalizability may be an issue because only Blacks and Whites were included in the analysis; - Funding: NIH, DHHS
Inoue-Choi, 2022^53^; United States; NIH-AARP Diet and Health Study; Analytic N=159,937; Participant characteristics:; - [underlined: Race and/or Ethnicity]:; 2.8% Black,; 1.5% Hispanic,; 93.6% White; 1.2% other race or ethnicity;; 0.9% unknown; - [underlined: SEP]: 40% college or postgrad education; - [underlined: Selection:] Excluded participants who completed risk factor questionnaire by a proxy; incomplete physical activity data;; - 100% participants were former smokers; 66.9% male; - 44% Overweight | - DP Age(s): 50 to 69 y at baseline; Mean age: 62.6 y; - DP(s) examined: Healthy Eating Index-2015 (HEI-2015); - DP Components: HEI-2015: Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; PUFA+MUFA/SFA. Negative: Refined Grains; Added Sugars; SFA; Sodium; - DP Method(s): Index; Comparisons: Categorical: quartiles of HEI-2015 | Follow-Up Duration: 18.9 y; HEI-2015 vs. CVD mortality, HR, 95% CI; Q1: REF; Q2: 1.00, 95% CI: 0.97, 1.04; Q3: 1.01, 95% CI: 0.98, 1.05; Q4: 1.03, 95% CI: 0.99, 1.07; Summary: NS/Null: HEI-2015 & CVD mortality among former smokers | - Did not account for: BMI, Physical activity, Alcohol (Different covariates in separate models); - Dietary assessment: Single time point measurement of exposure; - Outcome measurement: Medical record + National Death Index; - Single point exposure measurement; Participants were 100% former smokers and predominantly white - the findings may not be generalizable. BMI, Physical activity and alcohol are measured as part of different exposures and the composite exposure of diet, physical activity, BMI and alcohol were associated with CVD mortality; - Funding: NCI
Jiang, 2015^128^; United States; Framingham Offspring Study; Analytic N=2159; Participant characteristics:; - [underlined: Race and/or Ethnicity]: Primarily Caucasians; - [underlined: SEP]: NR; - [underlined: Selection:] Excluded participants with implausible energy intake and missing intake. Excluded participants with hypertension at exam 5; - 56% Female; - Mean BMI: 26.6 kg/m2 | - DP Age(s): 25 to 90 y at baseline; Mean age: 52.5 y; - DP(s) examined: DASH Score [Folsom, 2007]; - DP Components: DASH: Positive: Vegetables; Nuts, Seeds and Legumes; Fruit; Total Grains; Whole Grains; Low-Fat Dairy; Negative: Fish; Meat; Poultry; Sweets; Total fat; Saturated fat; Sodium; - DP Method(s): Index; - Comparisons: Categorical: quintile of DASH score; Continuous | Follow-Up Duration: 13.4 y; DASH score vs. annual change in BP, β, 95% CI; SBP; 0.5-3.5: REF; 4.0: 0.01, 95% CI: − 0.18, 0.19; 4.5 - 5.0: 0.07, 95% CI: −0.09, 0.22; 5.5: 0.16, 95% CI: −0.04, 0.36; 6.0-10.0: 0.10, 95% CI: −0.09, 0.28; Per-unit increase: 0.054; P-value: 0.028; DBP; 0.5-3.5: REF; 4.0: −0.01, 95% CI: − 0.12, 0.12; 4.5- 5.0: 0.03, 95% CI: −0.07, 0.13; 5.5: 0.02, 95% CI: −0.11, 0.13; 6.0-10.0: 0.05, 95% CI: −0.07, 0.17; Per-unit increase: 0.021; P-value: 0.191; DASH score vs. Incident hypertension, β, 95% CI; 0.5-3.5: REF; 4.0: 1.01, 95% CI: 0.81, 1.25; 4.5- 5.0: 0.95, 95% CI: 0.79, 1.14; 5.5: 1.10, 95% CI: 0.87, 1.39; 6.0-10.0: 0.91, 95% CI: 0.73, 1.14; P-trend: 0.878; Summary: Direct/Positive: DASH (per-unit increase) & annual changes in SBP;; Null/NS: DASH (categorical) & annual changes in SBP;; Null/NS: DASH (categorical, per-unit icrease) & annual changes in DBP;; Null/NS: DASH (categorical) & incident hypertension | - Did not account for: SEP; - Dietary assessment: Single time point measurement of exposure; although there was reasonable correlation with subsequent DASH scores; - Outcome measurement: BP measured twice and average was used; Incident hypertension ≥140 mmHg or DBP≥90 mmHg or use of current hypertension medication; - Generalizability, an issue since the participants were primarily Caucasians. Participants that initiated hypertension medication got censored and those that were excluded tended to be older, less physically active, drink more alcohol, have higher BMI, SBP and DBP. All participants consumed high levels of sodium, it was not possible to represent low-sodium component.; - Funding: NHLBI/NIH; ARS
Judd, 2013^54^; United States; REGARDS; Analytic N=28,151; Participant characteristics:; - [underlined: Race and/or Ethnicity]:; 58% White; 42% Black; - [underlined: SEP]: 8-25% with Income <20,000; - 25-50% College graduates; - [underlined: Selection:] Excluded participants with a selfreport of stroke and missing FFQ;; - 55% women | - DP Age(s): >45 y at baseline; Mean age >65: 40-63%; - DP(s) examined: Convenience, Healthy, Sweets/Fats, Southern, Alcohol/Salads; - DP Components: Convenience: Positive: Beans; Chinese food; Condiments; Desserts; Fish; Fried food; Fried potatoes; High fat dairy; Mexican dishes; Mixed dishes with meat; Organ meat; Pasta dishes; Pizza; Potatoes; Poultry; Processed meats; Red meat; Refined grains; Salty snacks; Shell fish; Soup; Sweet breakfast foods; Vegetables - green leafy; Vegetable mixed dishes; - Healthy: Positive: 100% fruit juice; Beans; Bread - Whole Grain; Cereal; Cereal-high fiber; Fish; Fruit; Lowfat dairy; Milk alternatives; Milk - Lowfat; Poultry; Refined grains; Salad dressing/sauces; Seeds, nuts; Soup; Vegetable - cruciferous; Vegetable - dark yellow; Vegetable - green leafy; Vegetable - other; Vegetable - tomato; Vegetable mixed dishes; Water; Yogurt; Negative: Alcohol (Beer); Pizza; Soda; - Sweets/Fats: Positive: Added fats; Bread; Bread - Whole Grain; Butter; Candy; Chocolate; Coffee; Condiments; Desserts; Fried potatoes; Highfat dairy; Margarine; Milk - Highfat; Miscellaneous sugar; Pasta dishes; Pizza; Potatoes; Processed meats; Red meat; Refined grains; Salty snacks; Seeds, nuts; Sweet breakfast foods; Tea; - Southern: Positive: 100% fruit juice; Added fats; Bread; Egg and egg dishes; Fried food; Fried potatoes; Milk - Highfat; Miscellaneous sugar; Organ meat; Processed meats; Red meat; Refined grains; Shell fish; Soda; SSB Negative: Cereal-high fiber; Coffee; Lowfat dairy; Milk - Lowfat; Vegetable - green leafy; Yogurt; - Alcohol/salads: Positive: Added fats; Beer; Butter; Coffee; Eggs and egg dishes; Fish; Condiments; Highfat dairy; Liquor; Processed meats; Red meat; Salad dressing/sauces; Seeds, nuts; Shell fish; Vegetable - green leafy; Vegetable - tomato; Alcohol (Wine); Negative: 100% fruit juice; Cereal; Desserts; Sugar-sweetened beverages; Vegetable - dark yellow; Vegetable mixed dishes; - DP Method(s): Factor/Cluster; Comparisons: Categorical, quartiles of each DP | Follow-Up Duration: 5.7 y; Convenience vs. stroke, HR, 95% CI; Q1: REF; Q2: 0.97, 95% CI: 0.76, 1.24; Q3: 0.96, 95% CI: 0.75, 1.25; Q4: 1.09, 95% CI: 0.82, 1.46; P-trend: 0.69; Plant-based vs. stroke, HR, 95% CI; Q1: REF; Q2: 0.80, 95% CI: 0.62, 1.02; Q3: 0.74, 95% CI: 0.57, 0.96; Q4: 0.85, 95% CI: 0.65, 1.12; P-trend: 0.20; Sweets/Fats vs. stroke, HR, 95% CI; Q1: REF; Q2: 0.99, 95% CI: 0.78, 1.27; Q3: 0.88, 95% CI: 0.68, 1.14; Q4: 0.72, 95% CI: 0.53, 0.99; P-trend: 0.04; Southern vs. stroke, HR, 95% CI; Q1: REF; Q2: 0.93, 95% CI: 0.71, 1.22; Q3: 1.12, 95% CI: 0.86, 1.47; Q4: 1.30, 95% CI: 0.97, 1.76; P-trend: 0.05; Alcohol/Salads vs. stroke, HR, 95% CI; Q1: REF; Q2: 0.91, 95% CI: 0.71, 1.17; Q3: 0.97, 95% CI: 0.75, 1.24; Q4: 0.93, 95% CI: 0.71, 1.23; P-trend: 0.71; Summary: Inverse: Sweets/Fats & Stroke; Null: Convenience & Stroke; Null: Plant-based & Stroke; Null: Southern & Stroke; Null: Alcohol/Salads & Stroke | - Did not account for: Anthropometry; - Dietary assessment: Single time point measurement of exposure; - Outcome measurement: Medical record abstraction + adjudication + Death certificates; - Authors have described “healthy” DP in the description of the pattern, but have discussed the results as “plant-based” DP. It is possible that both are the same, but it is unclear. Generalizability may be an issue since Whites and Blacks were only included. Single time point diet assessment with FFQ.; - Funding: NIH/NINDS
Juul, 2021^55^; United States; Framingham Heart Study; Analytic N=3003; Participant characteristics:; - [underlined: Race and/or Ethnicity]: Primarily Caucasians; - [underlined: SEP]: 39% ≤12 y education; - [underlined: Selection:] Excluded participants with preexisting CVD, missing CVD follow-up data;; - Participants were overweight: 27.3 kg/m2; Hypertension: 19%; Smokers: never 34%, 19% current, former 47%; - 55.1% women | - DP Age(s): Mean age: 53.5 y; - DP(s) examined: UPF, NOVA Classification System [Monteiro, 2019]; - DP Components: NOVA 4: Nondairy coffee whitener, ice cream, sherbet/ice milk, margarine, red chili sauce, hot dogs, hamburger, processed meats, cold breakfast cereals, commercially baked cookies, pies, and sweet rolls, doughnuts, brownies, breads, English muffins/bagels, muffins/biscuits, pancakes/waffles, French fries, chips, crackers, pizza, sugarsweetened and low-calorie carbonated beverages, punch/lemonade, liquor, chocolate, candy bars, candy without chocolate, popcorn, fried food away from home, meat sandwiches, yoghurt.; - DP Method(s): Index; Comparisons: Continuous, UPF intake (serv./d or serv./wk) | Follow-Up Duration: 18 y; UPF vs. CVD mortality, HR, 95% CI; 1.09, 95% CI: 1.02, 1.16; UPF vs. hard CVD, HR, 95% CI; 1.06, 95% CI: 1.02, 1.11; UPF vs. hard CHD, HR, 95% CI; 1.09, 95% CI: 1.03, 1.14; UPF vs. Overall CVD, HR, 95% CI; 1.04, 95% CI: 1.01, 1.07; Summary: Positive: UPF (NOVA 4, serv/d) & Hard CVD, hard CHD, overall CV, CVD mortality | - Did not account for: None (all); - Dietary assessment: Single time point measurement of exposure; - Outcome measurement: Medical record abstraction; - Single time point measure of exposure; Race and/or ethnicity not accounted for; Generalizability may be an issue since participants are primarily Caucasians with higher levels of education; - Funding: NIH/NHLBI
Kauffman, 2020^56^; United States; Strong Heart Family Study; Analytic N=1899; Participant characteristics:; - [underlined: Race and/or Ethnicity]: 100% American Indian (multi-tribal, other data NR); - [underlined: SEP]: 12.3y of education; - [underlined: Selection:] Excluded participants if they were missing diet, lipoproteins, diabetes data, incomplete or implausible energy intake data and missing key covariates of interest; 60% women; - Mean BMI: 31.3 kg/m2; Current or Former Smokers: 61% | - DP Age(s): ≥ 18 y; Mean age at baseline ~41 y; - DP(s) examined: Alternative HEI (AHEI)-2010 [Chiuve 2012]; - DP Components: AHEI-2010, Positive: Vegetables (not potatoes, French fries); Fruit; Nuts and Soy Protein; Cereal Fiber; White: Red Meat Ratio; PUFA:SFA; Multi-Vitamin Use. Negative: Trans-UFA. Neutral: Alcohol; - DP Method(s): Index; Comparisons: Continuous for AHEI (23 point, i.e., difference between 10th and 90th percentiles) | Follow-Up Duration: 4-8 y; AHEI vs. TG, β, 95% CI; Diabetes: 0.1, 95% CI: 0.0, 0.2; No diabetes: 0.00, 95% CI: −0.1, 0.1; P-interaction: 0.41; AHEI vs. HDL-C, β, 95% CI; Diabetes: 0.0, 95% CI: −0.1, 0.1; No diabetes: 0.0, 95% CI: 0.0, 0.1; P-interaction: 0.09; AHEI vs. LDL-C, β, 95% CI; Diabetes: −0.1, 95% CI: −0.2, −0.1; No diabetes: 0.0, 95% CI: 0.0, 0.1; P-interaction: 0.008; Summary: Inverse: AHEI (with diabetes) & LDL-C; Positive: AHEI (without diabetes) & LDL-C; Positive: AHEI (without diabetes) & HDL-C; NS/Null: AHEI and HDL-C (with diabetes); NS/Null: AHEI (with and without diabetes) & TG | - Did not account for: None (all); - Dietary assessment: Single time point measurement of exposure; - Outcome measurement: Unclear if biomarker is a fasting measurement; - Single measure of dietary recall; - Funding: NHLBI/NIH
Keaver, 2021^57^ United States; NHANES; Analytic N=36,825; Participant characteristics:; - [underlined: Race and/or Ethnicity]: 70% NHW; 11% NHB; 12.9% Hisp; 5.8 Other; - [underlined: SEP]: PIR (≥1.85): 63.3; <1.85: 30.2; College education and above: 57.5; Some college: 24.2; <High school: 18.4; - [underlined: Selection:] Excluded pregnant and lactating women, individuals with potentially unreliable dietary intake, implausible energy intake, individuals with no linked mortality data and those who died within 12 months of dietary assessment;; - Former smokers: 24.9%; Current smokers: 22.8%; - Mean BMI: 25.8 kg/m2; - Hypertension: 30.8%; - High cholesterol: 31.9% | - DP Age(s): 20+ y at baseline; Mean age: 47.1 y; - DP(s) examined: Comprehensive Diet Quality Index (cDQI); Plant-based Diet Quality Index (pDQI); Animal-based Diet Quality Index (aDQI); - DP Components: cDQI: Positive: Whole grains, vegetables excluding white potatoes, whole fruits, nuts/seeds/legumes, vegetable oils and coffee/tea, fish/seafood, dairy products and poultry; Negative: Refined grains, fruit juices, sugar-sweetened beverages and sweets/desserts, processed meats, unprocessed red meats and eggs; - pDQI: Positive: Whole grains, vegetables excluding white potatoes, whole fruits, nuts/seeds/legumes, vegetable oils and coffee/tea; Negative: Refined grains, fruit juices, sugar-sweetened beverages and sweets/desserts; - aDQI: Positive: Fish/seafood, dairy products and poultry; Negative: processed meats, unprocessed red meats and eggs; - DP Method(s): Index; Comparisons: Categorical, quartiles (Q1 ref) of and linear trend for cDQI, aCDQI, pCDQI | Follow-Up Duration: 8.3 y; Heart disease mortality cDQI; Q1: REF; Q2: 1.05, 95% CI: 0.74, 1.50; Q3: 1.03, 95% CI: 0.73, 1.45; Q4: 1.05, 95% CI: 0.72, 1.53; P-trend: 0.82; pDQI; Q1: REF; Q2: 0.85, 95% CI: 0.59, 1.22; Q3: 1.11, 95% CI: 0.78, 1.60; Q4: 0.95, 95% CI: 0.67, 1.35; P-trend: 0.80; aDQI; Q1: REF; Q2: 1.01, 95% CI: 0.74, 1.39; Q3: 1.02, 95% CI: 0.78, 1.32; Q4: 0.93, 95% CI: 0.65, 1.31; P-trend: 0.78; Summary: NS/Null: cDQI & heart disease mortality; Null/NS: pDQI & heart disease mortality; Null/NS: aDQI & heart disease mortality | - Did not account for: None (all); - Dietary assessment: Two consecutive 24 hr recalls; - Outcome measurement: Medical records + National Death Index; - Single time point measurement of diet (24-hr recall in-person); - Funding: NIH/NIMHD
Kim, 2018^59^; United States; NHANES; Analytic N=11,879; Participant characteristics:; - [underlined: Race and/or Ethnicity]:; ~75% NHW; ~10% NHB; ~6% Mexican American; ~9% Other; - [underlined: SEP]: Education:; <High school: ~18-26%; High school: ~29-37%; >High school: 37-46%; - Federal poverty level:; <130%: 14-20%; 130-350%: 44-46%; >350%: 34-36%; - [underlined: Selection:] Excluded participants with a history of stroke, heart attack, or ischemic heart disease, cancer, diabetes, chronic kidney disease.; - Overweight/Obesity: ~52%; - Current smoker: ~31%; - Former smoker: ~22%; - Hypertension: ~25% | - DP Age(s): 20 to 80 y at baseline; Mean age: 41 y; - DP(s) examined: Plant-Based Diet Index (PDI) [Kim 2018]; Healthy Plant-Based Diet Index (hPDI) [Kim 2018]; Unhealthy Plant-Based Diet Index (uPDI) [Kim 2018]; - DP Components: PDI: Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Negative: Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; - hPDI: Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Negative: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; - uPDI: Negative: Whole grains; Fruits; Vegetables; Nuts; Legumes; Vegetable oils; Tea/coffee; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; Positive: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; - DP Method(s): Index; Comparisons: Continuous (per 10-unit increase) of each DP | Follow-Up Duration: 19 y; PDI vs. CVD mortality, HR, 95% CI; All: 1.05, 95% CI: 0.99, 1.12; Men: 1.08, 95% CI: 0.99, 1.17; Women: 1.03, 95% CI: 0.96, 1.10; hPDI vs. CVD mortality, HR, 95% CI; All: 1.02, 95% CI: 0.97, 1.08; Men: 1.03, 95% CI: 0.96, 1.10; Women: 1.00, 95% CI: 0.93, 1.07; uPDI vs. CVD mortality, HR, 95% CI; All: 1.02, 95% CI: 0.96, 1.08; Men: 1.04, 95% CI: 0.96, 1.13; Women: 1.03, 95% CI: 0.95, 1.10; Summary: NS/Null: PDI & CVD mortality; NS/Null: hPDI & CVD mortality; NS/Null: uPDI & CVD mortality | - Did not account for: None (all); - Dietary assessment: Single time point measurement of exposure; - Outcome measurement: National Death Index; - Single time point measurement of diet; NHANES’s FFQ not validated; - Funding: NIDDK, JHSPH
Kim, 2019^58^; United States; ARIC Study; Analytic N=12,168; Participant characteristics:; - [underlined: Race and/or Ethnicity]: 27% Black; 73% White; - [underlined: SEP]: 68.3-85.1% high school graduates (stratified by DP); - [underlined: Selection:] Excluded participants with implausible energy intake, non-White or Black participants, without complete information on covariates, with with a history of myocardial infarction, heart or arterial surgery, heart failure, stroke, and cancer at baseline.; - Current smoker: ~25%; - Hypertension: ~32% | - DP Age(s): 45 to 64 y at baseline; Mean age: 53.8 y; - DP(s) examined: Plant-Based Diet Index (PDI) [Kim 2018]; Healthy Plant-Based Diet Index (hPDI) [Kim 2018]; Unhealthy Plant-Based Diet Index (uPDI) [Kim 2018]; Pro-vegetarian Diet Index [Martinez-Gonzalez 2014]; - DP Components: PDI: Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Negative: Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; - hPDI: Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Negative: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; - uPDI: Negative: Whole grains; Fruits; Vegetables; Nuts; Legumes; Vegetable oils; Tea/coffee; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; Positive: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; - Provegetarian Diet Index: Grains, fruits, vegetables, nuts, legumes, and potatoes, animal fat, dairy, eggs, fish or seafood, meat; - DP Method(s): Index; Comparisons: Categorical, quintiles of each DP | Follow-Up Duration: 25 y; PDI vs. CVD mortality, HR, 95% CI; Q1: REF; Q2: 0.85, 95% CI: 0.74, 0.99; Q3: 0.81, 95% CI: 0.70, 0.93; Q4: 0.74, 95% CI: 0.63, 0.87; Q5: 0.68, 95% CI: 0.58, 0.80; P-trend: <0.001; hPDI vs. CVD mortality, HR, 95% CI; Q1: REF; Q2: 0.97, 95% CI: 0.84, 1.12; Q3: 0.95, 95% CI: 0.82, 1.11; Q4: 0.83, 95% CI: 0.70, 0.99; Q5: 0.81, 95% CI: 0.68, 0.97; P-trend: 0.01; uPDI vs. CVD mortality, HR, 95% CI; Q1: REF; Q2: 0.95, 95% CI: 0.83, 1.10; Q3: 0.91, 95% CI: 0.78, 1.05; Q4: 0.82, 95% CI: 0.71, 0.96; Q5: 0.93, 95% CI: 0.80, 1.08; P-trend: 0.13; Provegetarian diet index vs. CVD mortality, HR, 95% CI; Q1: REF; Q2: 0.90, 95% CI: 0.79, 1.03; Q3: 0.78, 95% CI: 0.67, 0.91; Q4: 0.83, 95% CI: 0.72, 0.96; Q5: 0.69, 95% CI: 0.59, 0.81; P-trend: <0.001; PDI vs. CVD, HR, 95% CI; Q1: REF; Q2: 0.98, 95% CI: 0.89, 1.08; Q3: 0.96, 95% CI: 0.88, 1.04; Q4: 0.86, 95% CI: 0.78, 0.96; Q5: 0.84, 95% CI: 0.75, 0.92; P-trend: <0.001; hPDI vs. CVD, HR, 95% CI; Q1: REF; Q2: 1.01, 95% CI: 0.93, 1.11; Q3: 0.99, 95% CI: 0.91, 1.09; Q4: 1.01, 95% CI: 0.91, 1.11; Q5: 0.91, 95% CI: 0.82, 1.01; P-trend: 0.11; uPDI vs. CVD, HR, 95% CI; Q1: REF; Q2: 0.93, 95% CI: 0.85, 1.02; Q3: 0.99, 95% CI: 0.91, 1.09; Q4: 1.02, 95% CI: 0.94, 1.12; Q5: 0.94, 95% CI: 0.85, 1.04; P-trend: 0.98; Provegetarian vs. CVD, HR, 95% CI; Q1: REF; Q2: 0.94, 95% CI: 0.87, 1.03; Q3: 0.85, 95% CI: 0.77, 0.94; Q4: 0.90, 95% CI: 0.82, 0.99; Q5: 0.84, 95% CI: 0.76, 0.93; p<0.001; Summary: Inverse: PDI and CVD mortality; Inverse: hPDI and CVD mortality; Inverse: Provegetarian diet index and CVD mortality; Inverse: PDI and incident CVD; Inverse: Provegetarian diet index and incident CVD; Null: uPDI and CVD mortality; Null: hPDI and incident CVD; Null: uPDI and incident CVD | - Did not account for: None (all); - Dietary assessment: Multiple exposure assessment; - Outcome measurement: State registry + National Death Index; - Data inaccuracy concerns (BMI incorrectly reported); - Funding: NIH/NHLBI, NIDDK, JHSPH
Kim, 2019 UPF^60^; United States; NHANES; Analytic N=11,898; Participant characteristics:; - [underlined: Race and/or Ethnicity]:; 76% NHW; 10% NHB; 6% MA; 8% Other; - [underlined: SEP]: 18-20% <130%; - 21-25% < High school; - [underlined: Selection:] Excluded participants with missing information on UPF and mortality; Excluded participants with a chronic diease (selfreported diagnosis of heart attack, stroke or IHD, cancer, diabetes (using diabetes medication, self-report diabetes), CKD.; - Mean BMI: ~26 kg/m2; - Hypertension: 24-26%; - Current & former smokers: 53% | - DP Age(s): ≥20 years; Mean age: 41 y; - DP(s) examined: UPF, NOVA Classification System [Monteiro, 2019]; - DP Components: NOVA 4 (times/d): Chocolate milk, ice cream, ice milk, milkshakes, bacon, sausage, processed meats, sweetened cereals, spaghetti/pasta with tomato sauce, cheese dishes, pizza, calzone, lasagna, salted snacks, cakes, cookies, brownies, fruit juices, sugar-sweetened and artificially sweetened beverages (HiC, Tang, Koolaid, diet colas, diet sodas, regular colas and sodas), hard liquor, margarine; - DP Method(s): Index; Comparisons: Categorical, quartiles of UPF | Follow-Up Duration: 19 y; UPF vs. CVD mortality, HR, 95% CI; Q1: REF; Q2: 1.10, 95% CI: 0.69, 1.76; Q3: 0.94, 95% CI: 0.61, 1.45; Q4: 1.13, 95% CI: 0.74, 1.71; P-trend: 0.78; Summary: NS/Null: UPF & CVD mortality | - Did not account for: None (all); - Dietary assessment: Single time point measurement of exposure; - Outcome measurement: National Death Index; - FFQ not designed to answer research question on food processing. No validation of FFQ; Single time point measure of exposure; NHANES III was conducted several decades ago and food supply could have changed; - Funding: NIH/NIDDK
Kim, 2020^61^; United States; ARIC Study; Analytic N=8041; Participant characteristics:; - [underlined: Race and/or Ethnicity]: 20% Blacks; 80% White; - [underlined: SEP]: ~75% to 89% high school graduates; - [underlined: Selection]: Excluded participants with implausible total energy intake, missing hypertension classification at any f/u visits, those who are neither black or white, has hypertension at baseline, evidence of heart disease; - Overweight/Obesity: 57.5% | - DP Age(s): 45 to 64 y at baseline; Mean age: 53.2 y; - DP(s) examined: overall’ Plant-Based Diet Index (oPDI; healthy PDI, hPDI; unhealthy PDI, hPDI) [Kim 2018; Satija 2016]; Provegetarian DP index [Martinez-Gonzalez 2014]; PDI-Rotterdam [Chen, 2018]; - DP Components: PDI: Positive: Vegetables; Potatoes; Legumes; Fruit; Fruit Juices; Nuts; Whole Grains; Refined Grains; Tea and Coffee; Sugar-Sweetened and Artificially Sweetened Beverages; Sweets and Desserts. Negative: Fish or Seafood; Meat; Egg; Miscellaneous Animal Foods; Dairy; Animal Fat; - hPDI: Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Negative: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; - uPDI: Negative: Whole grains; Fruits; Vegetables; Nuts; Legumes; Vegetable oils; Tea/coffee; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; Positive: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; - Provegetarian: Positive: Whole grains, Refined grains; Vegetables; Potatoes; Legumes; Fruit; Nuts. Negative: Fish and Other Seafood; Meat; Eggs; Dairy; Animal Fats; - PDI-Rotterdam: Positive: Whole grains; Fruits; Vegetables; Nuts; Legumes; Coffee and tea; Vegetable oil (including margarine); Refined grain; Potatoes; Total SSB (Fruit juice; SSB); Sweets and desserts; Alcoholic beverage; Negative: Animal fat; Egg; Dairy; Fish or seafood; Meat; - DP Method(s): Index; Comparisons: Continuous (per-SD; linear trend); Categorical, Quintiles (Q1, HR: 1 ref) for PDI (oPDI, hPDI, uPDI), Provegetarian DP, and PDI-Rotterdam | Follow-Up Duration: 13 y; Overall PDI vs. hypertension, HR, 95% CI; Q1: REF; Q2: 0.94, 95% CI: 0.87, 1.02; Q3: 0.89, 95% CI: 0.83, 0.97; Q4: 0.88, 95% CI: 0.81, 0.96; Q5: 0.90, 95% CI: 0.83, 0.98; P-trend: 0.01; Per SD increment: 0.97, 95% CI: 0.94, 0.99; hPDI vs. hypertension, HR, 95% CI; Q1: REF; Q2: 0.93, 95% CI: 0.86, 1.00; Q3: 0.96, 95% CI: 0.89, 1.04; Q4: 0.95, 95% CI: 0.87, 1.04; Q5: 0.87, 95% CI: 0.80, 0.95; P-trend: 0.02; Per SD increment: 0.96, 95% CI: 0.93, 0.99; uPDI vs. hypertension, HR, 95% CI; Q1: REF; Q2: 1.06, 95% CI: 0.99, 1.16; Q3: 1.07, 95% CI: 0.98, 1.16; Q4: 1.09, 95% CI: 1.01, 1.19; Q5: 1.13, 95% CI: 1.04, 1.23; P-trend: 0.005; Per SD increment: 1.04, 95% CI: 1.01, 1.07; Provegetarian vs. hypertension, HR, 95% CI; Q1: REF; Q2: 0.95, 95% CI: 0.88, 1.03; Q3: 0.92, 95% CI: 0.85, 1.01; Q4: 0.93, 95% CI: 0.86, 1.00; Q5: 0.87, 95% CI: 0.80, 0.94; P-trend: 0.001; Per SD increment: 0.95, 95% CI: 0.92, 0.98; PDI-Rotterdam vs. hypertension, HR, 95% CI; Q1: REF; Q2: 1.01, 95% CI: 0.93, 1.09; Q3: 0.96, 95% CI: 0.88, 1.04; Q4: 0.97, 95% CI: 0.89, 1.06; Q5: 1.05, 95% CI: 0.97, 1.15; P-trend: 0.58; Per SD increment: 1.01, 95% CI: 0.98, 1.04; Summary: Inverse: PDI (Q3,Q4, Q5; per-SD) & hypertension; Inverse: hPDI (Q5; per-SD) & hypertension; Inverse: Provegetarian DP (Q5; per-SD) & hypertension; Positive: uPDI (Q4, Q5; per-SD) & hypertension; Null: PDI-Rotterdam & hypertension | - Did not account for: None(all); - Dietary assessment: Multiple exposure assessment; - Outcome measurement: Self-report + measurement; - Diet assessment twice via FFQ (not validated in ARIC); Hypertension is self-reported at least in some participants (potential for differential); Difference in baseline participants that were enrolled in the study and those that had incomplete outcome data. Some of the data in the FFQ is old and might not be reflective of the current food supply, especially margarine; - Funding: NIH/NHLBI, JHSPH, NIDDK
Kim, 2021^62^; United States; Framingham Heart Study; Analytic N=6360; Participant characteristics:; - [underlined: Race and/or Ethnicity]: Predominantly White; - [underlined: SEP]: 36-55% college educated;; - [underlined: Selection]: Excluded participants without FFQ and missing covariates at baseline, missing protein data;; - Current or former smokers: 42%; - Mean BMI: ~27 kg/m2 | - DP Age(s): 30 to 62 y at baseline; Mean age: 48-50 y; - DP(s) examined: Alternative HEI (AHEI)-2010 [Chiuve 2012];; - modified DASH Score [Fung 2008];; - Alternate Med Diet Score (aMED) [Fung 2005]; - DP Components: AHEI: Positive: Vegetables (not potatoes, French fries); Fruit; Nuts and Soy Protein; Cereal Fiber; White: Red Meat Ratio; PUFA: SFA; Multi-Vitamin Use. Negative: Trans-UFA. Neutral: Alcohol; - DASH, modified: Positive: Vegetables; Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Sodium; - aMED modified: Positive: Vegetables; Legumes; Fruit, Nuts; Whole grains; Fish; MUFA/SFA. Negative: Red and Processed Meat; Neutral: Alcohol; - DP Method(s): Index; Comparisons: Continuous, AHEI, DASH, or aMED | Follow-Up Duration: 14 y; AHEI vs. incident CVD, HR, 95% CI (part of mediation analysis) 0.98, 95% CI: 0.97, 0.99; P-value: 0.02; AHEI vs. CVD (fatal +non-fatal), HR, 95% CI 0.84, 95% CI: 0.76, 0.93; P-value: 1.2E-16; DASH vs. CVD (fatal +non-fatal), HR, 95% CI 0.82, 95% CI: 0.73, 0.91; P-value: 2.0E-04; MDS vs. CVD fatal +non-fatal), HR, 95% CI 0.89, 95% CI: 0.80, 0.98; P-value: 0.025; Summary: Inverse: AHEI & CVD; Inverse: DASH & CVD; Inverse: MDS & CVD | - Did not account for: Race and/or ethnicity (Predominantly White); - Dietary assessment: Single time point measurement of exposure; - Outcome measurement: Medical record abstraction + adjudication +Death certificates; - Generalizability may be an issue because the participants are predominantly middle-aged, White adults; Race and/or ethnicity was not accounted for; Single time point measure of exposure. This study primarily focused on mediation analysis, although supplement data provides an association between DPs and CVD (fatal +non-fatal); - Funding: NIH/NHLBI
Kong, 2021^63^; United States; Cardiovascular Disease Lifetime Risk Pooling Project (LRPP); Analytic N=30,219; Participant characteristics:; - [underlined: Race and/or Ethnicity]: Black: 24%; Others: NR; - [underlined: SEP]: 42%-65% College educated; - [underlined: Selection]: Excluded participants if they were underweight, had CVD at baseline, missing data or baseline intake was not performed; - Current & former smokers: 52% | - DP Age(s): ≥20 years; Mean: 53.5 y; - DP(s) examined: Alternative HEI (AHEI)-2010 [Chiuve 2012]; - DP Components: AHEI: Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; Fatty Acids. Negative: Refined Grains; Added Sugars in “Empty Calories”; Solid Fats in “Empty Calories”; Sodium; - DP Method(s): Index; Comparisons: Categorical, Quintiles of AHEI | Follow-Up Duration: 16.2 y; AHEI vs. incident CVD stratified by BMI, HR, 95% CI Normal BMI (18.5-24.9 kg/m2); Q1: REF; Q2: 0.96, 95% CI: 0.84, 1.10; Q3: 0.81, 95% CI: 0.70, 0.94; Q4: 0.81, 95% CI: 0.69, 0.93; Q5: 0.78, 95% CI: 0.66, 0.87; P-trend: <0.001; Overweight BMI (25.0-29.9 kg/m2), HR, 95% CI; Q1: REF; Q2: 0.90, 95% CI: 0.80, 1.01; Q3: 0.85, 95% CI: 0.74, 0.94; Q4: 0.81, 95% CI: 0.72, 0.92; Q5: 0.81, 95% CI: 0.72, 0.92; P-trend: 0.001; Obese BMI, HR, 95% CI; Q1: REF; Q2: 1.09, 95% CI: 0.96, 1.25; Q3: 1.06, 95% CI: 0.93, 1.21; Q4: 1.11, 95% CI: 0.97, 1.28; Q5: 1.14, 95% CI: 0.98, 1.32; P-trend: 0.09; AHEI vs. incident CVD stratified by BMI and race and/or ethnicity; Normal BMI, White, HR, 95% CI; Q1: REF; Q2: 0.95, 95% CI: 0.82, 1.11; Q3: 0.84, 95% CI: 0.72, 0.98; Q4: 0.85, 95% CI: 0.72, 0.99; Q5: 0.80, 95% CI: 0.68, 0.93; P-trend: 0.005; Overweight BMI, White, HR, 95% CI; Q1: REF; Q2: 0.91, 95% CI: 0.80, 1.03; Q3: 0.89, 95% CI: 0.78, 1.02; Q4: 0.83, 95% CI: 0.72, 0.95; Q5: 0.84, 95% CI: 0.73, 0.96; P-trend: 0.013; Obese BMI, White, HR, 95% CI; Q1: REF; Q2: 1.06, 95% CI: 0.90, 1.25; Q3: 1.11, 95% CI: 0.94, 1.30; Q4: 1.17, 95% CI: 0.99, 1.56; Q5: 1.20, 95% CI: 1.00, 1.43; P-trend: 0.051; Normal BMI, Black, HR, 95% CI; Q1: REF; Q2: 1.08, 95% CI: 0.81, 1.43; Q3: 0.84, 95% CI: 0.61, 1.17; Q4: 0.82, 95% CI: 0.57, 1.19; Q5: 0.83, 95% CI: 0.55, 1.25; P-trend: 0.37; Overweight, Black, HR, 95% CI; Q1: REF; Q2: 1.02, 95% CI: 0.80, 1.29; Q3: 0.82, 95% CI: 0.63, 1.06; Q4: 1.00, 95% CI: 0.77, 1.30; Q5: 0.88, 95% CI: 0.65, 1.19; P-trend: 0.88; Obese, Black, HR, 95% CI; Q1: REF; Q2: 1.17, 95% CI: 0.94, 1.45; Q3: 1.08, 95% CI: 0.86, 1.35; Q4: 1.10, 95% CI: 0.86, 1.40; Q5: 1.13, 95% CI: 0.86, 1.49; P-trend: 0.39; Summary: Inverse: AHEI & CVD incidence (normal BMI, overweight);; Inverse: AHEI & CVD (White: only normal BMI, overweight); Null: AHEI & CVD incidence (obesity);; Null: AHEI & CVD (White: obesity); Black (normal, overwight and obesity) | - Did not account for: Sex; - Dietary assessment: Single time point measurement of exposure; - Outcome measurement: Medical record abstraction + adjudication +Death certificates; - Single time point diet measure. Possible heterogeneity because of different cohorts used different dietary assessment methods; - Funding: NIH/NHLBI
Lara, 2019^64^; United States; REGARDS; Analytic N=16,068; Participant characteristics:; - [underlined: Race and/or Ethnicity]: 33.6% Black; - [underlined: SEP]: College graduate: ~26% to 53%;; - Income >75k: 20-30%; - [underlined: Selection]: Excluded participants with suspected heart failure (based on HF-related medications), those w/o HF follow-up, baseline HF undertermined and baseline CHD, active treatment for cancer, medical conditions preventing long-term participation or cognitive impairment, residence in nursing homes or on a waitlist for a nursing home and inability to communicate in English, without baseline form, complete FFQ; - 58.7% women;; - Mean BMI: ~29 kg/m2; - Hypertension: ~51%; - Dyslipidemia: ~55% | - DP Age(s): ≥45 y at baseline; Mean age: 64 y; - DP(s) examined: Convenience, Plant-based, Sweets/Fats, Southern, Alcohol/Salads; - DP Components: Convenience: Meat dishes, pasta, Mexican dishes, pizza, fried potatoes, Chinese dishes and fast food; - Plant-based: Cruciferous vegetables and other vegetables, fruit, beans, and fish; - Sweets/Fats: Desserts, bread, sweet breakfast foods, chocolate, candy, solid fats and oils, and miscellaneous sugar; - Southern: Fried food, organ meats, processed meats, eggs, added fats, and sugar-sweetened beverages; - Alcohol/Salads: Wine, liquor, beer, leafy greens and salad dressing; - DP Method(s): Factor/Cluster; Comparisons: Categorical, quartiles of each DP | Follow-Up Duration: 7.1 y; Plant-based vs total HF, HR, 95% CI; Q1: REF; Q2: 0.98, 95% CI: 0.73, 1.32; Q3: 0.89, 95% CI: 0.65, 1.21; Q4: 0.59, 95% CI: 0.41, 0.86; P-trend: 0.004; Plant-based vs HFrEF, HR, 95% CI; Q1: REF; Q2: 1.56, 95% CI: 0.99, 2.46; Q3: 1.40, 95% CI: 0.87, 2.27; Q4: 0.65, 95% CI: 0.35, 1.21; P-trend: 0.13; Plant-based vs HFpEF, HR, 95% CI; Q1: REF; Q2: 0.71, 95% CI: 0.43, 1.19; Q3: 0.68, 95% CI: 0.40, 1.15; Q4: 0.68, 95% CI: 0.38, 1.20; P-trend: 0.23; Convenience vs total HF, HR, 95% CI; Q1: REF; Q2: 0.94, 95% CI: 0.69, 1.30; Q3: 1.39, 95% CI: 1.02, 1.90; Q4: 1.21, 95% CI: 0.83, 1.77; P-trend: 0.17; Convenience vs HFrEF, HR, 95% CI; Q1: REF; Q2: 0.81, 95% CI: 0.49, 1.33; Q3: 1.39, 95% CI: 0.88, 2.20; Q4: 1.11, 95% CI: 0.63, 1.95; P-trend: 0.44; Convenience vs HFpEF, HR, 95% CI; Q1: REF; Q2: 1.14, 95% CI: 0.69, 1.89; Q3: 1.30, 95% CI: 0.76, 2.21; Q4: 1.33, 95% CI: 0.71, 2.52; P-trend: 0.35; Alcohol and Salads vs total HF, HR, 95% CI; Q1: REF; Q2: 0.74, 95% CI: 0.54, 1.00; Q3: 0.92, 95% CI: 0.68, 1.24; Q4: 0.83, 95% CI: 0.59, 1.16; P-trend: 0.45; Alcohol and Salads vs HFrEF, HR, 95% CI; Q1: REF; Q2: 0.84, 95% CI: 0.53, 1.34; Q3: 1.09, 95% CI: 0.70, 1.70; Q4: 0.83, 95% CI: 0.49, 1.38; P-trend: 0.65; Alcohol and Salads vs HFpEF, HR, 95% CI; Q1: REF; Q2: 0.51, 95% CI: 0.31, 0.85; Q3: 0.57, 95% CI: 0.34, 0.95; Q4: 0.65, 95% CI: 0.38, 1.12; P-trend: 0.12; Sweets vs total HF, HR, 95% CI; Q1: REF; Q2: 0.78, 95% CI: 0.57, 1.06; Q3: 0.86, 95% CI: 0.62, 1.19; Q4: 0.76, 95% CI: 0.51, 1.11; P-trend: 0.24; Sweets vs HFrEF, HR, 95% CI; Q1: REF; Q2: 0.64, 95% CI: 0.39, 1.03; Q3: 0.67, 95% CI: 0.41, 1.09; Q4: 0.69, 95% CI: 0.40, 1.20; P-trend: 0.29; Sweets vs HFpEF, HR, 95% CI; Q1: REF; Q2: 0.81, 95% CI: 0.48, 1.36; Q3: 1.02, 95% CI: 0.59, 1.77; Q4: 0.99, 95% CI: 0.51, 1.91; P-trend: 0.88; Southern vs total HF, HR, 95% CI; Q1: REF; Q2: 1.24, 95% CI: 0.88, 1.76; Q3: 1.02, 95% CI: 0.71, 1.45; Q4: 1.32, 95% CI: 0.90, 1.93; P-trend: 0.24; Southern vs HFrEF, HR, 95% CI; Q1: REF; Q2: 1.46, 95% CI: 0.85, 2.50; Q3: 1.26, 95% CI: 0.73, 2.18; Q4: 1.60, 95% CI: 0.90, 2.87; P-trend: 0.17; Southern vs HFpEF, HR, 95% CI; Q1: REF; Q2: 0.97, 95% CI: 0.56, 1.68; Q3: 0.74, 95% CI: 0.42, 1.32; Q4: 0.94, 95% CI: 0.51, 1.73; P-trend: 0.76; Summary: Inverse: Plant-based DP adherence & HF risk; Null/NS: Convenience and total HF; Null/NS: Alcohol and Salads and total HF; Null/NS: Sweets and total HF; Null/NS: Southern DP and total HF; Null/NS: Any DP and HF by ejection fraction | - Did not account for: None (all); - Dietary assessment: Single time point measurement of exposure; - Outcome measurement: Medical record abstraction + adjudication; - Diet measured only at baseline; Not generalizable to all U.S. population because it is restricted only to Whites and Blacks; - Funding: NIH/NINDS, NHLBI
Li, 2016^126^; United States; NHS II; Analytic N=3818; Participant characteristics:; - [underlined: Race and/or Ethnicity]: 93% White; - [underlined: SEP]: 100% Nurses and health professionals; - [underlined: Selection]: Excluded participants with a history of CVD or cancer at baseline, multiple gestations or pregnancies lasting less than 6 months, and those without a history of GDM. Also excluded women with a history of hypertension prior to the diagnosis of GDM, or missing data on post-pregnancy diet. Participants with a history of gestational diabetes mellitus; - Mean BMI: 26 kg/m2 | - DP Age(s): 24 to 44 y at baseline; Mean age: ~37 y; - DP(s) examined: Alternative HEI (AHEI)-2010 [Chiuve 2012]; Mediterranean Diet Score (MDS) [Trichopolou 2003]; DASH Score [Fung 2008]; - DP Components: AHEI: Positive: Vegetables (not potatoes, French fries); Fruit; Nuts and Soy Protein; Cereal Fiber; White: Red Meat Ratio; PUFA: SFA; Multi-Vitamin Use. Negative: Trans-UFA. Neutral: Alcohol; - MDS: Positive: Vegetables; Legumes; Fruit; Nuts; Cereals; Fish; MUFA/SFA; Negative: Red and Processed Meat; Dairy Products. Neutral: Alcohol; - DASH: Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Sodium; - DP Method(s): Index; - Comparisons: Categorical: Quartile of AHEI, MDS, DASH | Follow-Up Duration: 17 y; AHEI vs. hypertension, RR, 95% CI; Q1: REF; Q2: 0.80, 95% CI: 0.65, 0.97; Q3: 0.84, 95% CI: 0.69, 1.03; Q4: 0.76, 95% CI: 0.61, 0.94; P-trend: 0.03; DASH; Q1: REF; Q2: 0.82, 95% CI: 0.67, 1.01; Q3: 0.89, 95% CI: 0.73, 1.09; Q4: 0.72, 95% CI: 0.58, 0.90; P-trend: 0.01; MDS; Q1: REF; Q2: 0.90, 95% CI: 0.74, 1.09; Q3: 0.81, 95% CI: 0.65, 1.00; Q4: 0.70, 95% CI: 0.56, 0.88; P-trend: 0.002; Summary: Inverse: AHEI & incident hypertension; Inverse: DASH & incident hypertension; Inverse: MDS & incident hypertension | - Did not account for: BMI, SEP; - Dietary assessment: Multiple exposure assessment; - Outcome measurement: Generalizability may be an issue since participants were predominantly White and were health professionals and had GDM during pregnancy; Outcome is self-reported, although validated; - Funding: NIH
Li, 2018^67^; United States; NHS, HPFS; Analytic N=123,219; Participant characteristics:; - [underlined: Race and/or Ethnicity]: 96.2% White; - [underlined: SEP]: 100% Nurses and health professionals; - [underlined: Selection]: Excluded participants with implausible energy intake, BMI <18.5 kg/m2, missing value for BMI, physical activity, alcohol or smoking; - Current smoking: 16.8%; - Mean BMI: 25.1 kg/m2 | - DP Age(s): 30 to 55 y at baseline, NHS;; - 40 to 75 y at baseline, HPFS; - Mean age: 50 y; - DP(s) examined: Alternative HEI (AHEI)-2010 [Chiuve 2012];; - DP Components: AHEI: Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; Fatty Acids. Negative: Refined Grains; Added Sugars in “Empty Calories”; Solid Fats in “Empty Calories”; Sodium; - DP Method(s): Index; Comparisons: Categorical, quintiles of AHEI | Follow-Up Duration: 34 y; AHEI vs. CVD mortality, HR, 95% CI; Q1: REF; Q2: 0.89, 95% CI: 0.84, 0.94; Q3: 0.81, 95% CI: 0.76, 0.86; Q4: 0.75, 95% CI: 0.71, 0.80; Q5: 0.67, 95% CI: 0.63, 0.71; AHEI vs. heart disease mortality, HR, 95% CI 0.71, 95% CI: 0.70, 0.73; AHEI vs. stroke mortality, HR, 95% CI 0.72, 95% CI: 0.67, 0.77; Summary: Inverse: AHEI & CVD mortality, heart disease mortality, stroke mortality | - Did not account for: BMI, Physical activity, Smoking, Alcohol, SEP, Total E; - Dietary assessment: Multiple exposure assessment; - Outcome measurement: State registry + National Death Index + adjudicated; - Many KC were not accounted for, primarily because they were co-exposures. Participants were primarily white and health professionals, so the findings may not be entirely generalizable.; - Funding: NIH
Li, 2020^66^; United States; NHS, NHSII, HPFS; Analytic N=210,145; Participant characteristics:; - [underlined: Race and/or Ethnicity]: >~92% White; - [underlined: SEP]: 100% health professionals, nurses; - [underlined: Selection]: Excluded participants that had cancer, stroke, or CHD, that did not complete FFQ or met the exclusion criteria of FFQ (missing a certain amount of data; implausible energy intake); - Current and past smokers: ~47.3%; - Hypercholesterolemia: ~11.4%; - Hypertension: ~17.2% | - DP Age(s): 30 to 55 y at baseline, NHS; Mean age: ~51 y; - 25 to 42 y at baseline, NHSII; Mean age: ~37 y; - 40 to 75 y at baseline; Mean age: ~54 y; - DP(s) examined: Empirical dietary inflammatory pattern score (EDIP); - DP Components: Anti-inflammatory group: tea, coffee, dark yellow vegetables (carrots, or squash), leafy green vegetables (cabbage, spinach, or lettuce), snacks (cracker, or potato chips), fruit juice (apple juice, cantaloupe juice, orange juice, or other fruit juice), pizza; - Pro-inflammatory group: processed meat (sausage), red meat (beef, or lamb), organ meat (beef, calf, or chicken liver), other fish (canned tuna, or fish), other vegetables (mixed vegetables, green pepper, cooked mushroom, eggplant, zucchini, or cucumber), refined grains (white bread, biscuit, white rice, pasta, or vermicelli), high-energy and low energy beverages (cola with sugar, carbonated beverages with sugar, fruit punch drinks), and tomatoes; - DP Method(s): Index; Comparisons: Categorical, quintile of EDIP | Follow-Up Duration: 32 y; EDIP, quintiles vs. total CVD (fatal CHD + nonfatal MI + fatal and nonfatal stroke), HR, 95% CI; Q1: REF; Q2: 1.08, 95% CI: 1.02, 1.14; Q3: 1.15, 95% CI: 1.09, 1.22; Q4: 1.19, 95% CI: 1.13, 1.26; Q5: 1.38, 95% CI: 1.31, 1.46; P-trend: <0.001; EDIP, quintiles vs. total CHD (fatal CHD + nonfatal MI), HR, 95% CI; Q1: REF; Q2: 1.10, 95% CI: 1.02, 1.17; Q3: 1.20, 95% CI: 1.12, 1.28; Q4: 1.24, 95% CI: 1.16, 1.32; Q5: 1.46, 95% CI: 1.36, 1.56; P-trend: <0.001; EDIP, quintiles vs. stroke (fatal and nonfatal), HR, 95% CI; Q1: REF; Q2: 1.06, 95% CI: 0.97, 1.15; Q3: 1.09, 95% CI: 1.00, 1.19; Q4: 1.13, 95% CI: 1.04, 1.23; Q5: 1.28, 95% CI: 1.17, 1.39; P-trend: <0.001; Summary: Direct/Positive: EDIP scores and total CVD; Direct/Postive: EDIP scores and total CHD; Direct/Positive: EDIP scores and stroke | - Did not account for: None (all); - Dietary assessment: Multiple exposure assessment; - Outcome measurement: Medical record abstraction + adjudication +Death certificates; - Generalizability may be an issue because the participants are predominantly middle-aged, White adults. At least a third of participants were excluded because of missing FFQ data. Analyses stratified by cohort (sex) did not differ in findings from those in pooled analyses. EDIP includes alcohol (beer and wine). Separate model adjusting for alcohol in supp did not alter the association; - Funding: NCI/NIH, NHLBI, NIDDK
Li, 2022^65^; United States; NHANES; Analytic N=40,074; Participant characteristics:; - Race and/or Ethnicity:; - 46% NHW;; - 21% NHB;; - 7% Hispanic;; - 26% Other; - [underlined: SEP]: Education (stratified by DP) ≤ 12th grade: ~18 - 37% High school graduate: ~18-27%; More than high school: ~36-64%; - Family income to poverty (stratified by DP) <1.3: ~20-37% 1.3-3.5: ~32-34% ≥ 3.5: ~21-40%; - [underlined: Selection]: Excluded participants <18 y, had missing dietary data or implausible energy intake, or had no linked mortality data (n = 50) | - DP Age(s): 18 to 85 y at baseline; Mean age: 47.3 y; - DP(s) examined: Plant-Based Diet Index (PDI) [Satija, 2016]; Healthful PDI (hPDI) [Satija, 2016]; unhealthful PDI (uPDI) [Satija, 2016]; - DP Components: PDI: Positive : Vegetables; Potatoes; Legumes; Fruit; Fruit Juices; Nuts; Whole Grains; Refined Grains; Tea and Coffee; Sugar-Sweetened and Artificially Sweetened Beverages; Sweets and Desserts. Negative: Fish or Seafood; Meat; Egg; Miscellaneous Animal Foods; Dairy; Animal Fat; - hPDI: Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Negative: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; - uPDI: Negative: Whole grains; Fruits; Vegetables; Nuts; Legumes; Vegetable oils; Tea/coffee; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; Positive: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; - DP Method(s): Index; Comparisons: Continuous, Categorical, quintiles of PDI, hPDI and uPDI | Follow-Up Duration: 7.8 y; PDI vs. CVD mortality, HR, 95% CI; Q1: REF; Q2: 1.05, 95% CI: 0.86, 1.27; Q3: 0.84, 95% CI: 0.69, 1.02; Q4: 0.91, 95% CI: 0.75, 1.12; Q5: 0.84, 95% CI: 0.68, 1.04; P-trend: 0.046; hPDI vs. CVD mortality, HR, 95% CI; Q1: REF; Q2: 1.17, 95% CI: 0.91, 1.51; Q3: 1.11, 95% CI: 0.87, 1.41; Q4: 1.01, 95% CI: 0.79, 1.28; Q5: 1.09, 95% Ci: 0.85, 1.40; P-trend: 0.99; uPDI vs. CVD mortality, HR, 95% CI; Q1: REF; Q2: 1.05, 95% CI: 0.88, 1.26; Q3: 1.16, 95% CI: 0.96, 1.41; Q4: 1.05, 95% CI: 0.86, 1.29; Q5: 1.42, 95% CI: 1.12, 1.79; P-trend: 0.015; Summary: Inverse: PDI & CVD mortality; Direct/Positive: uPDI & CVD mortality; Null/NS: hPDI & CVD mortality | - Did not account for: None (all); - Dietary assessment: Two consecutive 24 hr recalls; - Outcome measurement: National Death Index + ICD codes; - Two 24 hr recalls, very close in time was used to measure dietary exposure. Data stratified by poverty, race, alcohol intake is presented, but did not extract because the data seems to be wrong (i.e. same effect sizes are presented for cancer and CVD mortality); - Funding: National Natural Science Foundation of China, Anhui Provincial Natural Science Foundation, Anhui Medical University
Liese, 2021^68^; United States; American Association of Retired Persons Diet and Health Study (AARP), the Multiethnic Cohort (MEC), and the Women’s Health Initiative Observational Study (WHI OS); Analytic N=64,226; Participant characteristics:; - [underlined: Race and/or Ethnicity]:; - AARP: 92.2% non-Hispanic White; 4.1% non-Hispanic Black; 3.7% other; - MEC: 24.2% Non-Hispanic White; 16% African American; 23.2% Latino; 29.4% Japanese American; 7.2% Native Hawaiian; - WHI: 84% non-Hispanic white; 7% Black; 4% Hispanic; 5% Other; - [underlined: SEP]: NR; - [underlined: Selection:] Excluded participants with implausible energy intake; Only with complete data on dietary intake, outcome status, or survival time were included | - DP Age(s): 45 to 79 y at baseline; - AARP: 50-71 y; - MEC: 45-75; - WHI: 50-79; - DP(s) examined: Healthy Eating Index (HEI-2015) [Krebs-Smith 2018]; Clustering; - DP Components: HEI-2015: Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; PUFA+MUFA/SFA. Negative: Refined Grains; Added Sugars; SFA; Sodium; - Constellation 1: Best diet quality, exceeding fruit goals, low dairy; - Constellation 2: Second best diet quality, exceeding fruit + sodium goals; - Constellation 3: Dairy adherers, greens & beans avoidance; - Constellation 4: Exceeding greens & beans, fruit and vegetables; - Constellation 5: Lowest rank diet, exceeding seafood & plant protein; - DP Method(s): Index; Other; Comparisons: Categorical, quintile of DP | Follow-Up Duration: 13-19 y; CVD-mortality; Constellation 1; MEC females cluster 1: 0.83, 95% CI: 0.72, 0.96; MEC males cluster 2: 0.75, 95% CI: 0.64, 0.89; Constellation 2; AARP females cluster 2: 0.74, 95% CI: 0.65, 0.84; AARP males cluster 2: 0.86, 95% CI: 0.78, 0.94; MEC females cluster 3: 0.74, 95% CI: 0.65, 0.85; MEC males cluster 3: 0.75, 95% CI: 0.67, 0.84; WHI OS cluster 3: 1.20, 95% CI: 0.90, 1.59; Constellation 3; WHI OS cluster 1: 1.11, 95% CI: 0.89, 1.40; Constellation 4; AARP females cluster 3: 0.80, 95% CI: 0.68, 0.95; AARP males cluster 3: 0.94, 95% CI: 0.82, 1.08; Constellation 5; AARP females cluster 1: 0.75, 95% CI: 0.61, 0.91; AARP males cluster 1: 0.86, 95% CI: 0.77, 0.96; MEC females cluster 2: 0.79, 95% CI: 0.66, 0.94; MEC males cluster 1: 0.74, 95% CI: 0.63, 0.88; WHI OS cluster 2: 0.91, 95% CI: 0.63, 1.30; Summary: Inverse: Constellation 1 (MEC female cluster 1, MEC males cluster 2) & CVD mortality; Inverse: Constellation 2 (AARP females cluster 2, AARP males cluster 2, MEC females cluster 3, MEC males cluster 3) & CVD mortality; Inverse: Constellation 4 (AARP females cluster 3) & CVD mortality; Inverse: Constellation 5 (AARP females cluster 1, AARP males cluster 1, MEC females cluster 2, MEC males cluster 1) & CVD mortality; Null/NS: Constellation 2 (WHI OS cluster 3) & CVD mortality; Null/NS: Constellation 4 (AARP males cluster 3) & CVD mortality; Null/NS: Constellation 3 (WHI OS cluster 1) & CVD mortality; Null/NS: Constellation 5 (WHI OS cluster 2) & CVD mortality | - Did not account for: None (all); - Dietary assessment Single time point measurement of exposure; - Outcome measurement: Medical record + National Death Index + adjudicated; - Unclear, but it looks like single point expsoure assessment. Different FFQs were used across cohorts, but it may not have been controlled for in the analyses. Unclear how participants that were not included in the analysis were similar or different than those that were included (i.e. those with complete dietary intake, outcome status or survival time); - Funding: NIH/NCI
Mattei, 2017^69^; United States; Boston; Puerto Rican Health Study; Analytic N=1137; Participant characteristics:; - [underlined: Race and/or Ethnicity]: 100% Puerto Ricans; - [underlined: SEP]: Ratio of income to poverty (stratified by DP): ~1.09 - 1.76; - Education >8th grade: 50-61%; - [underlined: Selection:] Excluded participants reporting outlying energy intakes or with questions left blank in the FFQ; Enrolled self-identified Puerto Rican, who were able to respond to home-based interview, and had no severe health conditions or cognitive impairment.; - BMI: ~31.2 kg/m2; - Obesity: 54%; - Hypertension: 66% | - DP Age(s): 45 to 75 y; Mean age (stratified by DP): ~57 y; - DP(s) examined: AHA Diet Score (AHA-DS) [Bhupathiraju 2011]; Alternative HEI (AHEI)-2010 [Chiuve 2012]; Healthy Eating Index (HEI-2005) [Guenther 2008]; Mediterranean Diet Score (MDS) [Trichopoulou 2003]; DASH diet modfied [modified Fung, 2008]; - DP Components: AHA-DS: Positive: Vegetables and Fruit; Variety; Whole Grains; Fish; Negative: SFA; Total fats; Trans Fat; Cholesterol; Added Sugars; Sodium; Neutral: Alcohol; - AHEI-2010: Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol; - HEI-2005: Positive: Total Vegetables; Dark Green/Orange Vegetables, Legumes; Total Fruit; Whole Fruit; Whole Grains; Total Grains; Meat and Beans; Milk, Yogurt, Cheese, and Soy Beverages; Healthy Oils. Negative: SFA; Solid fats, Alcohol, and Added Sugars; Sodium; - MDS: Positive: Vegetables; Legumes (and beans); Fruit (and; - Orange juice); Whole grains (oatmeal); Fish (traditional); MUFA/SFA (corn oil). Negative: Red and Processed Meat; Dairy Products (Whole Milk). Neutral: Alcohol (Beer); - DASH: Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Total dairy; Negative: Red and Processed Meat; Sweetened beverages; Sodium;; - DP Method(s): Index; Comparisons: Continuous: per unit in z-scores | Follow-Up Duration: 2 y; HDL cholesterol, mg/dl; AHA-DS: −0.07 [underlined: +] 0.26, P-value: 0.78; DASH: −0.51 [underlined: +] 0.26, P-value: 0.05; HEI: 0.13 [underlined: +] 0.27, P-value: 0.64; MeDS: −0.01 [underlined: +] 0.25, P-value: 0.96; AHEI: 0.04 [underlined: +] 0.26, P-value: 0.87; LDL cholesterol, mg/dl; AHA-DS: −0.04 [underlined: +] 0.94, P-value: 0.96; DASH: 0.80 [underlined: +] 0.92, P-value: 0.39; HEI: 1.54 [underlined: +] 0.94, P-value: 0.10; MeDS: 0.79 [underlined: +] 0.90, P-value: 0.38; AHEI: 0.71 [underlined: +] 0.91, P-value: 0.44; log-TG; AHA-DS: −0.01 [underlined: +] 0.01, P-value: 0.66; DASH: −0.003 [underlined: +] 0.01, P-value: 0.81; HEI: −0.02 [underlined: +] 0.01, P-value: 0.28; MeDS: −0.02 [underlined: +] 0.01, P-value: 0.21; AHEI: −0.01 [underlined: +] 0.01, P-value: 0.34; SBP, mmHg; AHA-DS: 0.33 [underlined: +] 0.54, P-value: 0.53; DASH: 0.34 [underlined: +] 0.53, P-value: 0.50; HEI: 0.23 [underlined: +] 0.53, P-value: 0.67; MeDS: −0.06 [underlined: +] 0.51, P-value: 0.91; AHEI: 0.26 [underlined: +] 0.52, P-value: 0.61; DBP, mmHg; AHA-DS: −0.11 [underlined: +] 0.30, P-value: 0.72; DASH: −0.18 [underlined: +] 0.29, P-value: 0.54; HEI: −0.43 [underlined: +] 0.29, P-value: 0.14; MeDS: −0.24 [underlined: +] 0.28, P-value: 0.40; AHEI: −0.05 [underlined: +] 0.29, P-value: 0.87; Summary: NS/Null: AHA-DS, DASH, HEI, MeDS, AHEI & BP, TC, HDL-C, LDL-C, log-TGs | - Did not account for: Anthropometry; - Dietary assessment: Single time point measurement of exposure; - Outcome measurement: Fasting lipid panel; Multiple measures of BP; - DP from validated-FFQ at baseline; Single time point measure of exposure. Anthropometry not accounted for in the model because it was another outcome considered; - Funding: NIH, NHLBI, NIA
Mursu, 2013^70^; United States; Iowa; Women’s Health Study; Analytic N=29,634; Participant characteristics:; - [underlined: Race and/or Ethnicity]: 99% White; - [underlined: SEP]: 51 to 66% High school or less; - [underlined: Selection:] Excluded participants with diabetes, CVD, cancer. Excluded participants that were premenopausal or did not complete baseline questionnaire; - 99% at baseline were postmenopausal women; - Current smoker: ~15%; - High BP: ~33%; - Mean BMI: 26.7 kg/m2 | - DP Age(s): 55 to 69 y; Mean age at baseline: 61.4 y; - DP(s) examined: Alternative HEI (AHEI)-2010 [Chiuve 2012]; - a priori diet quality score [Mursu, 2013]; - DP Components: AHEI- 2010, Positive: Vegetables; Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol; - a priori DQ score: Positive: Green Vegetables, Other Vegetables, Tomato; Legumes, Beans, Soy Products; Fruit; Nuts, Seeds; Whole Grains; Fish; Poultry; Low-Fat Dairy; Oil; Tea, Coffee; Beer, Wine, Liquor. Negative: Fried potatoes; Red Meat, Liver, Processed Meat, Butter; Whole-Fat Dairy; Soft Drinks, Sweets; Salty Snacks; Fried Foods. Neutral: Potatoes; Fruit Juices; Chocolate, Diet Soft Drinks; Eggs; Margarine; - DP Method(s): Index; Comparisons: Categorical, quartile of AHEI, a priori diet quality score | Follow-Up Duration: 20 y; AHEI vs. CVD mortality, HR, 95% CI; Q1: REF; Q2: 0.99, 95% CI: 0.91, 1.09; Q3: 0.91, 95% CI: 0.83, 1.00; Q4: 0.79, 95% CI: 0.72, 0.88; P-trend: <0.001; A priori score vs. CVD mortality, HR, 95% CI; Q1: REF; Q2: 0.92, 95% CI: 0.84, 1.01; Q3: 0.86, 95% CI: 0.78, 0.95; Q4: 0.79, 95% CI: 0.72, 0.88; P-trend: <0.001; After 18 y of follow-up; AHEI vs. CVD mortality, HR, 95% CI; Q1: REF; Q2: 1.05, 95% CI: 0.85, 1.29; Q3: 0.89, 95% CI: 0.71, 1.12; Q4: 0.72, 95% CI: 0.56, 0.93; P-trend: 0.002; After 18 y of follow-up; A priori score vs. CVD mortality, HR, 95% CI; Q1: REF; Q2: 0.95, 95% CI: 0.77, 1.17; Q3: 0.77, 95% CI: 0.62, 0.96; Q4: 0.61, 95% CI: 0.47, 0.80; P-trend: <0.001; Summary: Inverse: AHEI and CVD mortality; Inverse: a priori score and CVD mortality | - Did not account for: None (all); - Dietary assessment Multiple exposure assessment; - Outcome measurement: State registry + National Death Index + Medical record; - Generalizability may be an issue since all participants were older white women; - Funding: NIH, Academy of Finland, Finnish Cultural Foundation, Fulbright Program
Musicus, 2022^71^; United States; NHS II; Analytic N=90,884; Participant characteristics:; - [underlined: Race and/or Ethnicity]:>90% White; - [underlined: SEP]: >68% married; 100% nurses; - [underlined: Selection:] Excluded participants who had cancer, CVD at baseline, implausible energy intake; - Mean BMI: ~27.2 kg/m2; - Hypertension: 29.6%; - Hypercholesterolemia: 36.7% | - DP Age(s): 25 to 42 y at baseline; Mean age: ~57 y; - DP(s) examined: AHEI-2010, PDI, hPDI, uPDI; - DP Components: AHEI-2010: Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium (note: alcohol excluded); - PDI: Positive: Vegetables; Potatoes; Legumes; Fruit; Fruit Juices; Nuts; Whole Grains; Refined Grains; Tea and Coffee; Sugar-Sweetened and Artificially Sweetened Beverages; Sweets and Desserts. Negative: Fish or Seafood; Meat; Egg; Miscellaneous Animal Foods; Dairy; Animal Fat; - hPDI: Positive: Vegetables; Legumes; Fruit; Whole Grains; Sugar-Sweetened and Artificially Sweetened Beverages; Sweets and Desserts; Tea and Coffee. Negative: Potatoes; Refined Grains; Fish or Seafood; Meat; Fruit Juices; Egg; Miscellaneous Animal Foods; Dairy; Animal Fat; - uPDI: uPDI: Positive: Vegetables; Legumes; Fruit; Whole Grains; Sugar-Sweetened and Artificially Sweetened Beverages; Sweets and Desserts; Tea and Coffee. Negative: Potatoes; Refined Grains; Fish or Seafood; Meat; Fruit Juices; Egg; Misc. Animal Foods; Dairy; Animal Fat; - DP Method(s): Index; Comparisons: Categorical: Quintiles of AHEI-2010, PDI, hPDI, uPDI | Follow-Up Duration: 26 y; Overall PDI vs. CVD, RR, 95% CI; Q1: REF; Q2: 0.87, 95% CI: 0.76, 0.98; Q3: 0.83, 95% CI: 0.73, 0.95; Q4: 0.75, 95% CI: 0.66, 0.86; Q5: 0.74, 95% CI: 0.63, 0.85; P-trend: <0.0001; hPDI vs. CVD, RR, 95% CI; Q1: REF; Q2: 0.87, 95% CI: 0.76, 0.99; Q3: 0.80, 95% CI: 0.70, 0.92; Q4: 0.80, 95% CI: 0.70, 0.92; Q5: 0.71, 95% CI: 0.60, 0.83; P-trend: <0.0001; uPDI vs. CVD, RR, 95% CI; Q1: REF; Q2: 1.00, 95% CI: 0.87, 1.14; Q3: 0.98, 95% CI: 0.85, 1.13; Q4: 1.10, 95% CI: 0.96, 1.26; Q5: 1.15, 95% CI: 1.00, 1.33; P-trend: 0.023; AHEI-2010 vs. CVD, RR, 95% CI; Q1: REF; Q2: 0.97, 95% CI: 0.85, 1.11; Q3: 0.93, 95% CI: 0.81, 1.06; Q4: 0.85, 95% CI: 0.74, 0.98; Q5: 0.77, 95% CI: 0.66, 0.89; P-trend: <0.0001; Summary: Inverse: Overall PDI, hPDI, AHEI-2010 & CVD risk; Positive: uPDI & CVD risk | - Did not account for: None (all); - Dietary assessment: Multiple exposure assessment; - Outcome measurement: Outcome not reported in detail; - It is unclear whether participants had single vs. multiple dietary recall; - Funding: NIH/NCI, NHLBI
Nazari, 2018^72^; United States; MESA; Analytic N=5468; Participant characteristics:; - [underlined: Race and/or Ethnicity]:; 39% White; 23.5% Black; 18.5% Chinese; 18.9% Hispanic; - [underlined: SEP]: NR; - [underlined: Selection:] Excluded participants with diabetes, with incomplete dietary questionnaire; 46.4% males; - Smoker: 12.7%; - Hypertension: 23.6%; - Mean BMI: 27.4 kg/m2 45 to 84 y at baseline; Mean age: 61.8 y | - DP Age(s): 45 to 84 y at baseline; Mean age: 61.8 y; - DP(s) examined: RRR, PCS, PLS; - DP Components: RRR: Positive: Fats and oils; Poultry; Non-diet soda; Processed meat; Tomatoes; Legumes; Chicken, tuna, and egg salad; Friend potatoes; Negative: Dark-yellow vegetables; Cruciferous vegetables; - Principal component regression (PCR): Positive: Red meat; High-fat cheeses and sauces; Poultry; White bread; Tomatoes; Fats and oils; Fried potatoes; Processed meat; Other vegetables; Potato and pasta salad; - Partial Least squares (PLS): Positive: Fats and oils; Processed meat; High-fat cheeses and sauces; Fried potatoes; Non-diet soda; Tomatoes; Desserts; Poultry; Negative: Cruciferous vegetables; Dark-yellow vegetables; - DP Method(s): RRR; Comparisons: Categorical, quintile of RRR, PCR, PLS | RRR Factor 1 vs. Stroke, HR, 95% CI; Q1: REF; Q2: 5.66, 95% CI: 1.26, 25.38; Q3: 4.87, 95% CI: 1.06, 22.34; Q4: 5.97, 95% CI: 1.31, 27.07; Q5: 6.83, 95% CI: 1.51, 30.87; P-trend: 0.02; PCR 1; Q1: REF; Q2: 1.16, 95% CI: 0.43, 3.11; Q3: 2.65, 95% CI: 1.13, 6.18; Q4: 1.10, 95% CI: 0.37, 3.23; Q5: 1.47, 95% CI: 0.54, 3.96; P-trend: 0.44; PLS 1; Q1: REF; Q2: 2.51, 95% CI: 0.88, 7.09; Q3: 2.18, 95% CI: 0.74, 6.45; Q4: 3.08, 95% CI: 1.07, 8.88; Q5: 2.02, 95% CI: 0.63, 6.64; P-trend: 0.20; Summary: Positive/Direct: Dietary pattern score for RRR and stroke; NS/Null: PCR 1 DP, PLS DP and stroke | - Did not account for: Alcohol, Anthropometry; - Dietary assessment: Single time point measurement of exposure; - Outcome measurement: Outcome ascertainment unclear; - Funding: NHLBI
Neuhouser, 2023^73^; United States; WHI; Analytic N=100,374; Participant characteristics:; - [underlined: Race and/or Ethnicity]: 84.5% NHW; 7.7% NHB; 3.3% Hispanic/Latina; 2.8% Asian/Pacific Islander; - [underlined: SEP]: 42.4% ≥ college degree; - [underlined: Selection:] Excluded participants with a history of CVD; - Mean BMI: 27.6 kg/m2; - Current smoking: 6.2%; Past smoking: 43% | - DP Age(s): 50 to 79 y at baseline; Mean age of the total cohort: 63.6y; - DP(s) examined: HEI-2010; - DP Components: Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; Fatty Acids. Negative: Refined Grains; Added Sugars in “Empty Calories”; Solid Fats in “Empty Calories”; Sodium; - DP Method(s): Index; Comparisons: Continuous (Per 20% increase in HEI-2010 (Uncalibrated (Uncal) and Calibrated (Cal.) with biomarkers)) | Follow-Up Duration: ~20 y; Uncalibrated HEI-2010 (20% increment) vs.CVD mortality, HR, 95% CI; 0.94, 95% CI: 0.92, 0.96; Calibrated HEI-2010 (20% increment) vs. CVD mortality, HR, 95% CI; 1.07, 95% CI: 0.85, 1.34; HEI-2010 (Cal. per 20%) and:; Coronary heart disease, HR: 1.04, 95% CI: 0.72, 1.50; CABG/PCI, HR: 1.28, 95% CI: 0.91, 1.79; MI, HR: 1.00, 95% CI: 0.70, 1.41; Stroke, HR: 1.07, 95% CI: 0.83, 1.37; Hemorrhagic, HR: 1.28, 95% CI: 0.87, 1.90; Ischemic, HR: 1.02, 95% CI: 0.77, 1.35; Total CVD, HR: 1.14, 95% CI: 0.85, 1.53; HEI-2010 (Uncal. per 20%) and:; Coronary heart disease, HR: 0.91, 95% CI: 0.87, 0.94; CABG/PCI, HR: 0.96, 95% CI: 0.93, 1.00; MI, HR: 0.91, 95% CI: 0.87, 0.95; Stroke, HR: 0.96, 95% CI: 0.92, 1.00; Hemorrhagic, HR: 1.09, 95% CI: 0.97, 1.22; Ischemic, HR: 0.94, 95% CI: 0.89, 0.98; total CVD, HR: 0.95, 95% CI: 0.93, 0.97; Summary: Inverse: Uncalibrated HEI-2010 (20% increment) & CHD, MI, Ischemic, total CVD and CVD mortality; Null: Calibrated (20% increment) & CHD, MI, Ischemic, total CVD and CVD mortality | - Did not account for: None (all); - Dietary assessment: Multiple exposure assessment; - Outcome measurement: Medical record abstraction; - Predominantly participants are NHW, so the findings may not be generalizable.; - Funding: NIH/NHLBI
Noel, 2020^74^; United States; WHI; Analytic N=40,095; Participant characteristics:; - [underlined: Race and/or Ethnicity:] 51.9 % Caucasian 31.8 % African American 14.1% Hispanic/Latino 2.2% Other; - [underlined: SEP]: <College degree: 67.8 %; Annual income <$20k: 24.7 %; - [underlined: Selection:] Excluded participants with prior HF at baseline, invalid diet data, underweight, missing BMI, diet, smoking or physical activity data, missing day-to-event data and race and/or ethnicity data; - Hypertension: 33%; - Hyperlipidemia: 48.6%; - Mean BMI: 29.7 kg/m2; - Current smoker: 10% | - DP Age(s): 50 to 79 y at baseline; Mean age: 62.5 y; - DP(s) examined: AHEI-2010; - DP Components: AHEI-2010: Positive: Vegetables (not potatoes, French fries); Fruit; Nuts and Soy Protein; Cereal Fiber; White: Red Meat Ratio; PUFA:SFA; Multi-Vitamin Use. Negative: Trans-UFA. Neutral: Alcohol; - DP Method(s): Index; Comparisons: Categorical, Quintiles of AHEI vs. HFpEF, HFrEF | Follow-Up Duration: 14.5 y; AHEI score vs. HFpEF, HR, 95% CI; Q1: REF; Q2: 0.93, 95% CI: 0.79, 1.09; Q3: 0.96, 95% CI: 0.81, 1.13; Q4: 0.83, 95% CI: 0.69, 1.00; Q5: 0.80, 95% CI: 0.65, 0.97; P-trend: 0.06; AHEI score vs. HFrEF, HR, 95% CI; Q1: REF; Q2: 0.84, 95% CI: 0.67, 1.05; Q3: 0.94, 95% CI: 0.75, 1.17; Q4: 0.71, 95% CI: 0.54, 0.91; Q5: 0.61, 95% CI: 0.46, 0.82; P-trend: 0.0088; Summary: Inverse: AHEI & HFrEF; AHEI (Q5) & HFpEF; NS/Inverse: AHEI (Q4, Q3, Q2) & HFpEF | - Did not account for: None (all); Other: Total E; - Dietary assessment: Multiple exposure assessment; - Outcome measurement: Medical record abstraction; - Funding: NHLBI
Ogilvie, 2017^75^; United States; ARIC Study; Analytic N=14,082; Participant characteristics:; - [underlined: Race and/or Ethnicity]:; 74% White; 26% Black; - [underlined: SEP]: Education (stratified by sex); <High school: ~23-24%; High school: ~36-45%; >High school: ~33-40%; - [underlined: Selection:] Excluded participants with prevalent peripheral arterial disease (PAD), neither black nor white, those with implausible energy intake; - Current and Former smokers: 57.7%; - Hypertension: 33.9% | - DP Age(s): 45 to 64 y at baseline; Mean age: 54.1 y; - DP(s) examined: Western, Healthy DP; - DP Components: Western diet pattern: Positive: Processed meats, fried food, refined grains, red meat, eggs, dessert, high-fat dairy, sugar-sweetened beverages, fat, sweets, legumes, potatoes, ice cream, other vegetables, nuts & peanut butter, coffee, tomatoes, tea, dark-leaf vegetables, carotene vegetables; Negative: Diet soda, fish & seafood, poultry, cruciferous vegetables, fruits (excluding fruit juice), whole grains, low-fat dairy, yogurt; Neutral: Fruit juice; - Healthy diet pattern: Positive: Cruciferous vegetables, fruits (excluding fruit juice), carotene vegetables, other vegetables, fish & seafood, poultry, dark-leaf vegetables, whole grains, tomatoes, legumes, low-fat dairy, yogurt, fruit juice, potatoes, nuts & peanut butter, fat, diet soda, tea, high-fat dairy, red meat, dessert, ice cream; Negative: Sweets, eggs, coffee, processed meat, refined grains, fried food, sugar-sweetened beverages; - DP Method(s): Factor/Cluster; Comparisons: Categorical, quintiles of DP | Follow-Up Duration: 19.9 y; Western vs. PAD, HR, 95% CI; Q1: REF; Q2: 1.03, 95% CI: 0.87, 1.22; Q3: 1.14, 95% CI: 0.96, 1.37; Q4: 1.16, 95% CI: 0.95, 1.42; Q5: 1.23, 95% CI: 0.95, 1.59; P-trend: 0.07; Healthy vs. PAD, HR, 95% CI; Q1: REF; Q2: 1.13, 95% CI: 0.96, 1.33; Q3: 1.20, 95% CI: 1.02, 1.42; Q4: 1.32, 95% CI: 1.11, 1.56; Q5: 1.19, 95% CI: 1.00, 1.42; p-trend: 0.011; Summary: Positive/Direct: Healthy diet pattern & PAD; Null: Western diet pattern & PAD | - Did not account for: Alcohol, Anthropometry (just height); - Dietary assessment: Single time point measurement of exposure; - Outcome measurement: Medical record abstraction; - Dietary intake assessed at baseline only; alcohol intake was assessed & examined separately but not included in DP models; Only Blacks and Whites were included, so generalizability may be an issue; - Funding: NHLBI
Pang, 2021^76^; United States; CACTI; Analytic N=649; Participant characteristics:; - [underlined: Race and/or Ethnicity]: 90% White; Others: NR; - [underlined: SEP]: NR; - [underlined: Selection]: Excluded participants with implausible energy intake; - Current and past smoking: 26%; - Mean BMI: 27.2 kg/m2; - MetS: 39.8%; - Hypertension: 50.2%; - Hypertriglyceridemia: 38.2% | - DP Age(s): 19 to 56 y at baseline; Mean age: 38 y; - DP(s) examined: Empirical Dietary Inflammatory Pattern (EDIP); - DP Components: Anti-inflammatory group: tea, coffee, dark yellow vegetables (carrots, or squash), leafy green vegetables (cabbage, spinach, or lettuce), snacks (cracker, or potato chips), fruit juice (apple juice, cantaloupe juice, orange juice, or other fruit juice), pizza; - Pro-inflammatory group: processed meat (sausage), red meat (beef, or lamb), organ meat (beef, calf, or chicken liver), other fish (canned tuna, or fish), other vegetables (mixed vegetables, green pepper, cooked mushroom, eggplant, zucchini, or cucumber), refined grains (white bread, biscuit, white rice, pasta, or vermicelli), high-energy and low energy beverages (cola with sugar, carbonated beverages with sugar, fruit punch drinks), and tomatoes; - DP Method(s): Index; Comparisons: Categorical, tertiles of EDIP) | Follow-Up Duration: 14.6 y; EDIP (tertile) vs. Hypertension, β + SE; T1D participants; T2: −0.23 ± 0.27; P-value: 0.40; T3: −0.02 ± 0.26; P-value: 0.93; Non-diabetics; T2: −0.30 ± 0.25; P-value: 0.24; T3: −0.16 ± 0.28; P- value: 0.57; EDIP (tertile) vs. Low HDL-C, β + SE; T1D participants; T2: 0.37 ± 0.27; P-value: 0.18; T3: 0.73 ± 0.26; P-value: <0.01; Non-diabetics; T2: 0.39 ± 0.23; P-value: 0.09; T3: 0.53 ± 0.25; P-value: 0.03; EDIP (tertile) vs. Hypertriglyceridemia, β + SE; T1D participants; T2: 0.61 ± 0.31; P-value: 0.05; T3: 0.84 ± 0.30; P-value: <0.01; Non-diabetics; T2: 0.21 ± 0.26; P-value: 0.42; T3: 0.69 ± 0.27; P-value: 0.01; Summary: Direct/Positive: EDIP (Tertile 3 vs. Tertile 1) and low HDL-C, triglyceridemia in both T1D diabetics and non-diabetics;; Null: EDIP (Tertile 2 vs. Tertile 1; Tertile 3 vs. Tertile 1) and hypertension in both T1D and non-diabetics; Null: EDIP (Tertile 2 vs. Tertile 1) and low HDL-C, triglyceridemia in both T1D diabetics and nondiabetics; | - Did not account for: SEP; - Dietary assessment: Multiple exposure assessment; - Outcome measurement: Fasting lipid panel; - Diet was measured at 2 time-points - baseline and year 14 (when outcomes were measured). It looks like the mean EDIP score (calculated based on year 0 and year 14) was used in the assessment, which could mean that part of the data is cross-sectional. It is unclear whether participants changed their diets based on their diagnosis?! Also the authors have reported that participants over 40 with diabetes are prescribed lipid lowering drugs, which could have weakened the pro-inflammatory effects from diets. Although the authors adjusted for medication use, it is unclear if the diet would have been different; - Funding: NHLBI, ADA, Diabetes Endocrinology Research Center Clinical Investigation Core
Panizza, 2018^77^; United States; Multiethnic Cohort Study; Analytic N=156,804; Participant characteristics:; - [underlined: Race and/or Ethnicity]:; 24.2% White; 16% African American; 23.2% Latino; 29.4% Japanese American; 7.2%Native Hawaiian; - [underlined: SEP]: Education (stratified by DP) in men: 24-39%; - Education (stratified by DP) in women: 19-31%; - [underlined: Selection]: Excluded participants with a history of cancer, heart attack, stroke, with no valid dietary assessment info. Only participants with one of the MEC ethnic groups - white, African American, Japanese American, Native Hawaiian and Latino were included | - DP Age(s): 45 to 75 y at baseline; Mean age: 59.2 y; - DP(s) examined: HEI-2015 (Krebs-Smith, 2018); - DP Components: HEI-2015: Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; PUFA+MUFA/SFA. Negative: Refined Grains; Added Sugars; SFA; Sodium; - DP Method(s): Index; Comparisons: Categorical: quintiles of HEI-2015 | Follow-Up Duration: 17-22 y; HEI-2015 vs. CVD mortality, HR, 95% CI Men; Q1: REF; Q2: 0.90, 95% CI: 0.84, 0.96; Q3: 0.88, 95% CI: 0.82, 0.94; Q4: 0.84, 95% CI: 0.78, 0.90; Q5: 0.76, 95% CI: 0.71, 0.82; p<0.0001; Men, White; Q1: REF; Q2: 0.86, 95% CI: 0.73, 1.00; Q3: 0.80, 95% CI: 0.69, 0.94; Q4: 0.74, 95% CI: 0.64, 0.85; Q5: 0.65, 95% CI: 0.56, 0.75; p-trend: <0.0001; Men, African American; Q1: REF; Q2: 0.82, 95% CI: 0.70, 0.96; Q3: 0.84, 95% CI: 0.72, 0.98; Q4: 0.78, 95% CI: 0.67, 0.91; Q5: 0.66, 95% CI: 0.57, 0.77; p-trend: <0.0001; Men, Native Hawaiian; Q1: REF; Q2: 0.74, 95% CI: 0.59, 0.94; Q3: 0.88, 95% CI: 0.70, 1.11; Q4: 0.83, 95% CI: 0.66, 1.05; Q5: 0.88, 95% CI: 0.69, 1.11; p-trend: NS; Men, Japanese American; Q1: REF; Q2: 0.96, 95% CI: 0.85, 1.09; Q3: 0.83, 95% CI: 0.73, 0.94; Q4: 0.85, 95% CI: 0.75, 0.96; Q5: 0.81, 95% CI: 0.71, 0.93; p-trend: <0.001; Men, Latina; Q1: REF; Q2: 0.98, 95% CI: 0.85, 1.12; Q3: 1.00, 95% CI: 0.87, 1.14; Q4: 0.94, 95% CI: 0.82, 1.07; Q5: 0.95, 95% CI: 0.81, 1.10; p-trend: NS; Women; Q1: REF; Q2: 0.93, 95% CI: 0.87, 1.00; Q3: 0.88, 95% CI: 0.82, 0.95; Q4: 0.83, 95% CI: 0.77, 0.89; Q5: 0.75, 95% CI: 0.70, 0.81; p<0.0001; Women, White; Q1: REF; Q2: 0.87, 95% CI: 0.74, 1.03; Q3: 0.87, 95% CI: 0.75, 1.02; Q4: 0.68, 95% CI: 0.58, 0.80; Q5: 0.63, 95% CI: 0.54, 0.74; p-trend: <0.0001; Women, African American; Q1: REF; Q2: 0.92, 95% CI: 0.80, 1.05; Q3: 0.81, 95% CI: 0.71, 0.93; Q4: 0.86, 95% CI: 0.75, 0.98; Q5: 0.67, 95% CI: 0.59, 0.77; p-trend: <0.0001; Women, Native Hawaiian; Q1: REF; Q2: 0.97, 95% CI: 0.75, 1.25; Q3: 0.85, 95% CI: 0.66, 1.11; Q4: 0.93, 95% CI: 0.72, 1.21; Q5: 0.95, 95% CI: 0.73, 1.23; p-trend: NS; Women, Japanese American; Q1: REF; Q2: 1.02, 95% CI: 0.88, 1.18; Q3: 0.95, 95% CI: 0.82, 1.10; Q4: 0.84, 95% CI: 0.72, 0.98; Q5: 0.84, 95% CI: 0.73, 0.98; p-trend: <0.01; Women, Latina; Q1: REF; Q2: 0.86, 95% CI: 0.74, 1.00; Q3: 0.86, 95% CI: 0.73, 1.00; Q4: 0.82, 95% CI: 0.70, 0.97; Q5: 0.96, 95% CI: 0.81, 1.14; p-trend: <0.05; Summary: Inverse: HEI-2015 & CVD-mortality in women and men; Inverse: HEI-2015 & CVD-mortality in women (White, African American, Japanese American) and men (White, African American, Japanese American); Null: HEI-2015 & CVD mortality in women and men (Native Hawaiian, Latino) | - Did not account for: None (all); - Dietary assessment: Single time point measurement of exposure; - Outcome measurement: National Death Index + ICD codes; - Single time point diet measurement; Findings may not be entirely generalizable because only Japanese Americans were included; - Funding: NIH
Park, 2016 IJO^79^; United States; NHANES; Analytic N=1739; Participant characteristics:; - [underlined: Race and/or Ethnicity]:; 72.8% NHW; 14.1% NHB; 6% MA; 6.9% Other; - [underlined: SEP]: Metabolically healthy obese; - Education attainment:; <12y: 24.3%; 12 y: 40.0%; ≥3y: 35.8%; - Income:; PIR ≤1.3: 21.2%; PIR≤3.5: 42.2%; PIR>3.5: 36.5%; - Metabolically unhealthy obese; - [underlined: Selection]: Excluded participants with a history of MI, stroke, congestive heart failure, cancer. Excluded participants who reported changing their dietary patterns during the previous 12 months because of pre-existing obesity, high BP, high blood cholesterol, diabetes mellitus or general health. Excluded participants with implausible extreme energy intake, hs-CRP >10 mg l, BMI>60 kg m2, or pregnant or lactating.; - Participants with complete data on FFQ, 24-hr recall, those with complete data on cardiometabolic parameters including fasting glucose, insulin, blood pressure (BP), triglycerides, high-density lipoprotein cholesterol (HDL-C) and high-sensitivity C-reactive protein (hs-CRP) were included.; - 100% of participants with obesity (BMI≥30 kg/m2).; - Current or former smokers: 53.2%; - Hypertension: 40.5%; - BMI: 34.3 kg/m2 | - DP Age(s): 20 to 88 y at baseline; Mean age: 45 y; - DP(s) examined: Mediterranean Diet Score (MedDietScore) [Panagiotakas, 2007]; - DP Components: MDS: Positive: Vegetables; Legumes; Fruit; Whole Grains; Fish; MUFA: SFA. Negative: Red and Processed Meat; Poultry; Dairy products; alcohol; - DP Method(s): Index; Comparisons: Continuous, per 5pt increase, Categorical: tertiles of MDS vs. CVD mortality | Follow-Up Duration: 18.5 y; CVD mortality; MDS vs. CVD death, HR, 95% CI (Metabolically Healthy Obese); T1: REF; T2: 0.18, 95% CI: 0.05, 0.58; T3: 1.25, 95% CI: 0.41, 3.83; P-trend: 0.65; 5pt increase: 1.01, 95% CI: 0.29, 3.51; MDS vs. CVD death, HR, 95% CI (Metabolically Unhealthy Obese); T1: REF; T2: 1.28, 95% CI: 0.61, 2.67; T3: 1.61, 95% CI: 0.56, 4.62; P-trend: 0.34; 5pt increase: 1.15, 95% CI: 0.87, 1.54; Summary: NS/Null: MDS & CVD mortality in metabolically healthy and unhealthy participants with obesity | - Did not account for: None (all); - Dietary assessment: Single time point measurement of exposure; - Outcome measurement: National Death Index + ICD codes; - MDS scoring has not been validated in the population of interest; Single time-point exposure measurement; Very small numbers of reported outcomes, resulting in wider Cis. Multiple analysis of the exposure-outcome relationship, conducted for a different sub-group; - Funding: NR
Park, 2016^78^; United States; NHANES; Analytic N=2103; Participant characteristics:; - [underlined: Race and/or Ethnicity]: 79.4% NHW; Other: NR; - [underlined: SEP]: Education (>12 y); - Metabolically obese normal weight: 69%; - Metabolically healthy normal weight: 85.1%; - Income (PIR>1.3); - Metabolically obese normal weight: 81.6%; - Metabolically healthy normal weight: 87.8%; - [underlined: Selection]: Excluded participants with a history of MI, stroke, congestive heart failure, cancer. Excluded individuals who died during the first year of follow-up, those who reported implausible extreme energy intakes, pregnant or lactating women, and those with an hs-CRP level greater than 10 mg/L. Only normal weight participants with complete dietary data, cardiometabolic parameters were included (fasting glucose, insulin, TG. HDL-C, BP, hs-CRP).; - Current smoker: 28.8%; - Hypertension: 23.8% | - DP Age(s): 30 to 90 y at baseline; Mean age: ~48 y; - DP(s) examined: HEI [Kennedy, 1995]; - DASH [Sacks, 2001]; - DP Components: HEI: Positive: Vegetables; Fruit; Grains. Negative: Meat; Milk; Total Fat, SFA, Cholesterol. Neutral: Sodium; - DASH: Positive: Fruits, Vegetables, Nuts and legumes, low-fat dairy, whole grains; Negative: Total/saturated fat, sodium, sweets and red meats; - DP Method(s): Index; Comparisons: Continuous, per SD, Categorical: tertiles | Follow-Up Duration: 18.6 y; CVD mortality; Metabolically obese normal weight HEI vs. CVD mortality, HR, 95% CI; T1: REF; T2: 0.74, 95% CI: 0.47, 1.17; T3: 0.51, 95% CI: 0.30, 0.84; p-trend: 0.01; Per SD: 0.79, 95% CI: 0.65, 0.97; DASH vs. CVD mortality, HR, 95% CI; T1: REF; T2: 0.82, 95% CI: 0.57, 1.17; T3: 0.41, 95% CI: 0.26, 0.66; p-trend: <0.001; Per SD: 0.72, 95% CI: 0.55, 0.94; Metabolically Healthy Normal Weight HEI vs. CVD mortality, HR, 95% CI; T1: REF; T2: 0.66, 95% CI: 0.19, 2.36; T3: 0.91, 95% CI: 0.22, 3.73; p-trend: 0.44; Per SD: 0.77, 95% CI: 0.48, 1.23; DASH vs. CVD mortality, HR, 95% CI; T1: REF; T2: 0.65, 95% CI: 0.32, 1.33; T3: 1.17, 95% CI: 0.51, 2.70; p-trend: 0.67; Per SD: 1.07, 95% CI: 0.77, 1.48; Summary: Inverse: DASH, HEI in metabolically obesity normal weight phenotype & CVD-mortality; Null: DASH, HEI in metabolically healthy normal weight phenotype & CVD mortality | - Did not account for: None (all); - Dietary assessment: Single time point measurement of exposure; - Outcome measurement: National Death Index + ICD codes; - Single time point measure of exposure; Limited only to those who were normal weight, so the findings may not be generalizable; Multiple analysis of the exposure-outcome relationship, conducted for a different sub-group; - Funding: NR
Patel, 2021^80^; United States; Physicians’ Health Study (PHS) I and II; Analytic N=15,768; Participant characteristics:; - [underlined: Race and/or Ethnicity]: Mostly Caucasian male; - [underlined: SEP]: All physicians; - [underlined: Selection]: Excluded participants without FFQ and any component of MED, DASH, aHEI indices. Physicians who completed PHS I and II.; - Mean BMI: 25.8 kg/m2; - Current smoker: 3.3%; - Hypertension: 45.9% | - DP Age(s): 40 to 85 y at baseline; Mean age: 65.9 y; - DP(s) examined: aMED (Alternate Med Diet Score) [Fung 2005];; - DASH Score [Fung 2008];; - AHEI (Alternative Healthy Eating Index) [McCullough 2000]; - DP Components: aMED: Positive: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA/SFA. Negative: Red and Processed Meat. Neutral: Alcohol; - DASH: Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Sodium; - AHEI: Positive: Vegetables (not potatoes, French fries); Fruit; Nuts and Soy Protein; Cereal Fiber; White: Red Meat Ratio; PUFA: SFA; Multi-Vitamin Use. Negative: Trans-UFA. Neutral: Alcohol; - DP Method(s): Index; Comparisons: Categorical: quintile of aMED, DASH, AHEI score | Follow-Up Duration: 9.8 y; CVD mortality; MED diet score vs. CVD mortality, HR, 95% CI; Q1: REF; Q2: 0.99, 95% CI: 0.75, 1.30; Q3: 0.91, 95% CI: 0.69, 1.20; Q4: 0.73, 95% CI: 0.54, 0.99; Q5: 0.71, 95% CI: 0.53, 0.94; P-trend: 0.004; DASH diet score vs. CVD mortality, HR, 95% CI; Q1: REF; Q2: 1.14, 95% CI: 0.85, 1.54; Q3: 0.98, 95% CI: 0.73, 1.32; Q4: 0.91, 95% CI: 0.67, 1.25; Q5: 0.85, 95% CI: 0.62, 1.17; P-trend: 0.12; AHEI diet score vs. CVD mortality, HR, 95% CI; Q1: REF; Q2: 0.84, 95% CI: 0.64, 1.10; Q3: 0.88, 95% CI: 0.67, 1.14; Q4: 0.71, 95% CI: 0.52, 0.95; Q5: 0.55, 95% CI: 0.40, 0.76; P-trend: <0.001; Summary: Inverse: aMED & CVD mortality;; Inverse: AHEI & CVD mortality;; NS/Null: DASH score & CVD-mortality | - Did not account for: Race and/or ethnicity (Mostly Caucasian); - Dietary assessment: Single time point measurement of exposure; - Outcome measurement: Medical records + adjudication; - Funding: NIH/NHLBI, NCI
Rai, 2023^81^; United States; MASALA; Analytic N=735; Participant characteristics:; - [underlined: Race and/or Ethnicity]: 100% South Asian ancestry; - [underlined: SEP]: 68-81% with family income $75K +; 84-90% with BS degree+; - [underlined: Selection]: Excluded participants with CVD at baseline, reporting implausible energy intakes.; - Current smokers: ~3%; - BMI: ~26 kg/m2; - Hyperlipidemia: ~80%; - Hypertension: ~40% | - DP Age(s): 40 to 84 y at baseline; Mean age: 55.2 y; - DP(s) examined: South-Asian Mediterranean-style (SAM) diet score; - DP Components: Positive: Vegetables, fruits, legumes, nuts, whole grains, fish, and monounsaturated to saturated fat ratio; Moderation: Alcohol (5 g/d to 25 g/d); Negative: Red/processed meats; - DP Method(s): Index; Comparisons: Continuous SAM diet score, per 1-unit increase | Follow-Up Duration: 5 y; β(SE); Triglycerides: −0.39(0.90); HDL-C: −0.6 (0.21); LDL-C: −0.72 (0.74); Summary: NS/Null: SAM diet score is not associated with TG, HDL-C and LDL-C | - Did not account for: None (all); - Dietary assessment: Single time point measurement of exposure; - Outcome measurement: Multiple measure of BP; Unclear if lipid profile is measured while fasting?; - Diet was measured only at one time point (i.e. baseline); Unclear if lipid profile is measured while fasting?; - Funding: NIH, Canadian Insitutes of Health Research
Rebholz, 2020^82^; United States; Framingham Heart Study; Analytic N=3267; Participant characteristics:; - [underlined: Race and/or Ethnicity]: Primarily Caucasian; - [underlined: SEP]: NR; - [underlined: Selection]: Excluded participants who declined storage of their data in the NHLBI specimen and data repository information coordinating center, those that did not attend exam 5, with missing dietary data and with prevalent CVD; - Mean BMI: 27.4 kg/m2; - Current smoking: ~18.9%; - Hypertension: 21.1% | - DP Age(s): Mean age: 55 y; - DP(s) examined: HEI 1990, 2005, 2010, 2015 (HEI), alternative HEI, 2000 and 2010; - DP Components: HEI-1990: Positive: Vegetables; Fruit; Grains; Variety. Negative: Meat; Milk; Total Fat, SFA, Cholesterol. Neutral: Sodium; - AHEI-2000: Positive: Vegetables (not potatoes, French fries); Fruit; Nuts and Soy Protein; Cereal Fiber; White: Red Meat Ratio; PUFA: SFA; Multi-Vitamin Use. Negative: Trans-UFA. Neutral: Alcohol; - HEI-2005: Positive: Total Vegetables; Dark Green/Orange Vegetables, Legumes; Total Fruit; Whole Fruit; Whole Grains; Total Grains; Meat and Beans; Milk, Yogurt, Cheese, and Soy Beverages; Healthy Oils. Negative: SFA; Solid fats, Alcohol, and Added Sugars; Sodium; - AHEI-2010: Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol; - HEI-2010: Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; Fatty Acids. Negative: Refined Grains; Added Sugars in “Empty Calories”; Solid Fats in “Empty Calories”; Sodium; - HEI-2015: Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; PUFA+MUFA/SFA. Negative: Refined Grains; Added Sugars; SFA; Sodium; - DP Method(s): Index; Comparisons: Continuous, Tertiles of each DP | Follow-Up Duration: 17 y; HEI-1990 vs. CVD, HR, 95% CI; T1: REF; T2: 0.83, 95% CI: 0.68, 1.03; T3: 0.76, 95% CI: 0.61, 0.94; P-trend: 0.01; Continuous (per 10 points): 0.90, 95% CI: 0.82, 0.99; AHEI-2000 vs. CVD, HR, 95% CI; T1: REF; T2: 0.87, 95% CI: 0.71, 1.07; T3: 0.71, 95% CI: 0.57, 0.89; p-trend: 0.003; Continuous (per 10 points): 0.88, 95% CI: 0.80, 0.96; HEI-2005 vs. CVD, HR, 95% CI; T1: REF; T2: 0.94, 95% CI: 0.76, 1.17; T3: 0.75, 95% CI: 0.59, 0.94; P-trend: 0.01; Continuous (per 10 points): 0.87, 95% CI: 0.77, 0.99; AHEI-2010 vs. CVD, HR, 95% CI; T1: REF; T2: 0.81, 95% CI: 0.66, 0.99; T3: 0.77, 95% CI: 0.63, 0.96; p-trend: 0.02; Continuous (per 10 points): 0.90, 95% CI: 0.82, 0.98; HEI-2010 vs. CVD, HR, 95% CI; T1: REF; T2: 0.85, 95% CI: 0.69, 1.04; T3: 0.81, 95% CI: 0.65, 1.01; P-trend: 0.06; Continuous (per 10 points): 0.89, 95% CI: 0.81, 0.99; HEI-2015 vs. CVD, HR, 95% CI; T1: REF; T2: 0.76, 95% CI: 0.62, 0.94; T3: 0.73, 95% CI: 0.59, 0.91; P-trend: 0.004; Continuous (per 10 points): 0.87, 95% CI: 0.79, 0.96; HEI-1990 vs. CAD, HR, 95% CI; T1: REF; T2: 1.07, 95% CI: 0.82, 1.40; T3: 0.96, 95% CI: 0.72, 1.27; P-trend: 0.76; Continuous (per 10 points): 0.97, 95% CI: 0.86, 1.09; AHEI-2000 vs. CAD, HR, 95% CI; T1: REF; T2: 0.99, 95% CI: 0.76, 1.27; T3: 0.61, 95% CI: 0.45, 0.82; p-trend: 0.002; Continuous (per 10 points): 0.84, 95% CI: 0.75, 0.95; HEI-2005 vs. CAD, HR, 95% CI; T1: REF; T2: 0.83, 95% CI: 0.63, 1.09; T3: 0.75, 95% CI: 0.56, 1.00; P-trend: 0.05; Continuous (per 10 points): 0.90, 95% CI: 0.77, 1.05; AHEI-2010 vs. CAD, HR, 95% CI; T1: REF; T2: 0.81, 95% CI: 0.62, 1.05; T3: 0.67, 95% CI: 0.50, 0.88; p-trend: 0.005; Continuous (per 10 points): 0.86, 95% CI: 0.77, 0.95; HEI-2010 vs. CAD, HR, 95% CI; T1: REF; T2: 0.71, 95% CI: 0.54, 0.93; T3: 0.67, 95% CI: 0.51, 0.89; P-trend: 0.004; Continuous (per 10 points): 0.84, 95% CI: 0.74, 0.95; HEI-2015 vs. CAD, HR, 95% CI; T1: REF; T2: 0.68, 95% CI: 0.52, 0.90; T3: 0.68, 95% CI: 0.51, 0.89; P-trend: 0.004; Continuous (per 10 points): 0.83, 95% CI: 0.74, 0.94; HEI-1990 vs. stroke, HR, 95% CI; T1: REF; T2: 0.723, 95% CI: 0.49, 1.10; T3: 0.83, 95% CI: 0.56, 1.23; P-trend: 0.37; Continuous (per 10 points): 0.97, 95% CI: 0.81, 1.16; AHEI-2000 vs. stroke, HR, 95% CI; T1: REF; T2: 0.81, 95% CI: 0.54, 1.23; T3: 1.13, 95% CI: 0.75, 1.68; P-trend: 0.55; Continuous (per 10 points): 1.00, 95% CI: 0.84, 1.19; HEI-2005 vs. stroke, HR, 95% CI; T1: REF; T2: 1.15, 95% CI: 0.77, 1.71; T3: 0.79, 95% CI: 0.51, 1.22; P-trend: 0.27; Continuous (per 10 points): 0.88, 95% CI: 0.70, 1.10; AHEI-2010 vs. stroke, HR, 95% CI; T1: REF; T2: 0.82, 95% CI: 0.54, 1.23; T3: 1.06, 95% CI: 0.72, 1.57; P-trend: 0.74; Continuous (per 10 points): 1.00, 95% CI: 0.85, 1.17; HEI-2010 vs. stroke, HR, 95% CI; T1: REF; T2: 0.75, 95% CI: 0.50, 1.12; T3: 0.78, 95% CI: 0.52, 1.15; P-trend: 0.21; Continuous (per 10 points): 0.88, 95% CI: 0.73, 1.06; HEI-2015 vs. stroke, HR, 95% CI; T1: REF; T2: 0.84, 95% CI: 0.57, 1.24; T3: 0.70, 95% CI: 0.47, 1.05; P-trend: 0.09; Continuous (per 10 points): 0.88, 95% CI: 0.74, 1.05; HEI-1990 vs. heart failure, HR, 95% CI; T1: REF; T2: 0.77, 95% CI: 0.53, 1.12; T3: 0.77, 95% CI: 0.54, 1.12; P-trend: 0.19; Continuous (per 10 points): 0.88, 95% CI: 0.75, 1.04; AHEI-2000 vs. heart failure, HR, 95% CI; T1: REF; T2: 0.87, 95% CI: 0.61, 1.24; T3: 0.79, 95% CI: 0.54, 1.15; P-trend: 0.22; Continuous (per 10 points): 0.85, 95% CI: 0.73, 1.00; HEI-2005 vs. heart failure, HR, 95% CI; T1: REF; T2: 0.79, 95% CI: 0.55, 1.13; T3: 0.69, 95% CI: 0.47, 1.00; P-trend: 0.05; Continuous (per 10 points): 0.81, 95% CI: 0.66, 1.00; AHEI-2010 vs. heart failure, HR, 95% CI; T1: REF; T2: 0.71, 95% CI: 0.50, 1.01; T3: 0.66, 95% CI: 0.46, 0.94; P-trend: 0.02; Continuous (per 10 points): 0.83, 95% CI: 0.72, 0.96; HEI-2010 vs. heart failure, HR, 95% CI; T1: REF; T2: 0.62, 95% CI: 0.43, 0.89; T3: 0.63, 95% CI: 0.44, 0.90; P-trend: 0.01; Continuous (per 10 points): 0.83, 95% CI: 0.70, 0.98; HEI-2015 vs. heart failure, HR, 95% CI; T1: REF; T2: 0.48, 95% CI: 0.33, 0.70; T3: 0.65, 95% CI: 0.46, 0.91; P-trend: 0.01; Continuous (per 10 points): 0.82, 95% CI: 0.70, 0.96; Summary: Inverse: HEI-1990, AHEI-2000, HEI-2005, AHEI-2010, HEI-2010, HEI-2015 (tertiles and continuous) and CVD; Inverse: AHEI-2000, AHEI-2010, HEI-2010, HEI-2015 (tertiles and continuous) and CVD; Inverse: AHEI-2010, HEI-2010, HEI-2015 (tertiles and continuous) and heart failure; NS/Null: HEI-1990 (tertile, continuous), HEI-2005 (tertile and continuous) and CAD; NS/Null: HEI-1990, AHEI-2000, HEI-2005, AHEI-2010, HEI-2010, HEI-2015 (tertiles and continuous) and stroke; NS/Null: HEI-1990, AHEI-2000, HEI-2005 and heart failure | - Did not account for: Physical activity, SEP; - Dietary assessment: Single time point measurement of exposure; - Outcome measurement: Outcome not reported in detail; - Many KC were not accounted for. Physical activity and SEP was not reported, nor was it accounted for in the analysis. Diet was measured only in one instance. Outcome not reported in detail; - Funding: NHLBI/NIH, NIDDK
Reedy, 2014^83^; United States; NIH-AARP Diet and Health Study; Analytic N=424,662; Participant characteristics:; - [underlined: Race and/or Ethnicity]: White: 91%; - [underlined: SEP]: Education:; Men, college graduate (stratified by DP): ~32-56%; Women, college graduate (stratified by DP): ~21-38%; - [underlined: Selection]: Excluded participants with a history of cancer, heart disease, extreme caloric intake. Also excluded questionnaires completed by proxies; - Mean BMI: 25.9 kg/m2; - Former or current smoker: ~63.3% | - DP Age(s): 50 to 71 y at baseline; Mean age: 62.1 y; - DP(s) examined: AHEI-2010 (Alternative HEI 2010) [Chiuve, 2012]; - aMED (Alternate Med Diet Score) [Fung, 2009]; - DASH Score [Fung, 2008]; - HEI-2010 [Guenther, 2013]; - DP Components: AHEI-2010: Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: alcohol; - aMED: Positive: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA/SFA. Negative: Red and Processed Meat. Neutral: alcohol; - DASH: Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened beverages; Sodium; - HEI-2010: Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; Fatty Acids. Negative: Refined Grains; Added Sugars in “Empty Calories” Solid Fats in “Empty Calories”; Sodium; - DP Method(s): Index; Comparisons: Continuous, Categorical: quintiles | Follow-Up Duration: 15 y; Men, HEI-2010 vs. CVD mortality, HR, 95% CI; Q1: REF; Q2: 0.95, 95% CI: 0.91, 1.00; Q3: 0.90, 95% CI: 0.86, 0.95; Q4: 0.89, 95% CI: 0.85, 0.94; Q5: 0.85, 95% CI: 0.80, 0.89; Men, AHEI-2010 vs. CVD mortality, HR, 95% CI; Q1: REF; Q2: 0.88, 95% CI: 0.84, 0.93; Q3: 0.89, 95% CI: 0.85, 0.93; Q4: 0.82, 95% CI: 0.78, 0.86; Q5: 0.74, 95% CI: 0.70, 0.78; Men, aMED vs. CVD mortality, HR, 95% CI; Q1: REF; Q2: 0.92, 95% CI: 0.87, 0.97; Q3: 0.90, 95% CI: 0.86, 0.95; Q4: 0.85, 95% CI: 0.81, 0.90; Q5: 0.80, 95% CI: 0.76, 0.84; Men, DASH vs. CVD mortality, HR, 95% CI; Q1: REF; Q2: 0.95, 95% CI: 0.90, 1.00; Q3: 0.91, 95% CI: 0.86, 0.95; Q4: 0.88, 95% CI: 0.84, 0.92; Q5: 0.86, 95% CI: 0.81, 0.91; Women, HEI-2010 vs. CVD mortality, HR, 95% CI; Q1: REF; Q2: 0.90, 95% CI: 0.85, 0.97; Q3: 0.87, 95% CI: 0.81, 0.93; Q4: 0.82, 95% CI: 0.76, 0.88; Q5: 0.79, 95% CI: 0.73, 0.85; Women, AHEI-2010 vs. CVD mortality, HR, 95% CI; Q1: REF; Q2: 0.91, 95% CI: 0.85, 0.97; Q3: 0.81, 95% CI: 0.75, 0.86; Q4: 0.84, 95% CI: 0.79, 0.90; Q5: 0.72, 95% CI: 0.67, 0.78; Women, aMED vs. CVD mortality, HR, 95% CI; Q1: REF; Q2: 0.92, 95% CI: 0.86, 0.99; Q3: 0.89, 95% CI: 0.83, 0.95; Q4: 0.80, 95% CI: 0.75, 0.87; Q5: 0.78, 95% CI: 0.72, 0.84; Women, DASH vs. CVD mortality, HR, 95% CI; Q1: REF; Q2: 0.82, 95% CI: 0.82, 0.95; Q3: 0.84, 95% CI: 0.89, 0.89; Q4: 0.80, 95% CI: 0.74, 0.86; Q5: 0.78, 95% CI: 0.72, 0.83; Summary: Inverse: HEI-2010, AHEI-2010, aMED, DASH & CVD-mortality (Men and Women) | - Did not account for: None (all); - Dietary assessment: Single time point measurement of exposure; - Outcome measurement: SSA death file + National Death Index + SEER coding; - Single measure of dietary recall collected at baseline; - Funding: NR
Reedy, 2018^77^; United States; NIH-AARPDPMP; Analytic N=422,928; Participant characteristics:; - [underlined: Race and/or Ethnicity]: NR; - [underlined: SEP]: NR; - [underlined: Selection]: Excluded participants with a history of cancer, heart disease, extreme caloric intake. Also excluded questionnaires completed by proxies. Participants without at least one reliable dietary record was excluded | - DP Age(s): ≥ 20 y; - DP(s) examined: HEI-2015 (Healthy Eating Index) [Krebs-Smith 2018]; - DP Components: HEI-2015 Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; PUFA+MUFA/SFA. Negative: Refined Grains; Added Sugars; SFA; Sodium; - DP Method(s): Index; Comparisons: Categorical: quintiles of HEI-2015 | Follow-Up Duration: 15 y; Men, HEI-2015 vs. CVD mortality, HR, 95% CI; Q1: REF; Q2: 1.00, 95% CI: 0.95, 1.05; Q3: 0.95, 95% CI: 0.90, 1.00; Q4: 0.90, 95% CI: 0.85, 0.94; Q5: 0.87, 95% CI: 0.83, 0.92; Women, HEI-2015 vs. CVD mortality, HR, 95% CI; Q1: REF; Q2: 0.92, 95% CI: 0.86, 0.99; Q3: 0.89, 95% CI: 0.83, 0.95; Q4: 0.82, 95% CI: 0.76, 0.88; Q5: 0.79, 95% CI: 0.73, 0.85; Summary: Inverse: HEI-2015 & CVD-mortality (Women & Men) | - Did not account for: None (all); - Dietary assessment: Single time point measurement of exposure; - Outcome measurement: SSA death file + National Death Index + SEER coding; - Education, sex, income is NR. Single time point measure of exposure.; - Funding: None
Santiago-Torres, 2021^85^; United States; WHI; Analytic N=334; Participant characteristics:; - [underlined: Race and/or Ethnicity]: 100% Mexican descent; - [underlined: SEP]: Education:; 71% College degree or higher; - Income:; - 22% ≥75k; 40% 35-75k; - [underlined: Selection]: Excluded participants with MetS and diabetes at baseline, those with either low or high self-reported energy intake; - Mean BMI: 26.9 kg/m2; 64% Overweight/Obesity; - Current/Former smokers: 30% | - DP Age(s): 50 to 79 y at baseline; Mean age: 58 y; - DP(s) examined: aMED; DASH HEI-2010; MeDS; MexD; - DP Components: aMED: Positive: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA/SFA. Negative: Red and Processed Meat. Neutral: Alcohol; - DASH: Positive: Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Sodium; - HEI-2010: Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; Fatty Acids. Negative: Refined Grains; Added Sugars in “Empty Calories”; Solid Fats in “Empty Calories”; Sodium; - MeDS: Positive: Vegetables; Fruit, Nuts and legumes; Cereals; Fish; Whole grains; Meat; Dairy Products; MUFA/SFA; Neutral: Alcohol; - MexD: Positive: Corn tortillas; Beans; Soups; Mexican-mixed dishes; Vegetables; Whole fruits; Rice; Full-fat milk & Mexican dishes; Negative: Oils; Solid fats and added sugars; Processed meats; Refined grains; - DP Method(s): Index; Comparisons: Categorical: Tertiles of DP | Follow-Up Duration: NR; aMED score (tertiles) vs. elevated TG, OR, 95% CI; High: REF; Moderate: 1.10, 95% CI: 0.50, 2.44; Low: 0.98, 95% CI: 0.46, 2.09; DASH score (tertiles) vs. elevated TG, OR (95% CI); High: REF; Moderate: 0.52, 95% CI: 0.24, 1.14; Low: 0.95, 95% CI: 0.45, 2.01; HEI-2010 (tertiles) vs. elevated TG, OR (95% CI); High: REF; Moderate: 1.08, 95% CI: 0.50, 2.34; Low: 0.97, 95% CI: 0.44, 2.14; MeDS (tertiles) vs. elevated TG, OR, 95% CI; High: REF; Moderate: 0.90, 95% CI: 0.39, 2.06; Low: 1.18, 95% CI: 0.57, 2.44; MexS (tertiles) vs. elevated TG, OR, 95% CI; High: REF; Moderate: 1.21, 95% CI: 0.56, 2.62; Low: 1.41, 95% CI: 0.66, 3.01; aMED score (tertiles) vs. reduced HDL cholesterol, OR, 95% CI; High: REF; Moderate: 0.91, 95% CI: 0.36, 2.30; Low: 1.06, 95% CI: 0.46, 2.41; DASH score (tertiles) vs. reduced HDL cholesterol, OR, 95% CI; High: REF; Moderate: 1.04, 95% CI: 0.43, 2.50; Low: 1.27, 95% CI: 0.53, 3.06; HEI-2010 (tertiles) vs. reduced HDL cholesterol, OR, 95% CI; High: REF; Moderate: 1.72, 95% CI: 0.70, 4.23; Low: 1.48, 95% CI: 0.60, 3.69; MeDS (tertiles) vs. reduced HDL cholesterol, OR, 95% CI; High: REF; Moderate: 0.94, 95% CI: 0.38, 2.30; Low: 1.40, 95% CI: 0.61, 3.19; MexS (tertiles) vs. reduced HDL cholesterol, OR, 95% CI; High: REF; Moderate: 0.36, 95% CI: 0.15, 0.87; Low: 0.78, 95% CI: 0.34, 1.78; aMED (tertiles) vs. elevated BP, OR, 95% CI; High: REF; Moderate: 1.44, 95% CI: 0.70, 2.98; Low: 1.31, 95% CI: 0.65, 2.63; DASH (tertiles) vs. elevated BP, OR, 95% CI; High: REF; Moderate: 1.46, 95% CI: 0.73, 2.91; Low: 1.25, 95% CI: 0.61, 2.58; HEI-2010 (tertiles) vs. elevated BP, OR, 95% CI; High: REF; Moderate: 1.01, 95% CI: 0.48, 2.11; Low: 1.68, 95% CI: 0.82, 3.43; MeDS score (tertiles) vs. elevated BP, OR, 95% CI; High: REF; Moderate: 1.26, 95% CI: 0.60, 2.66; Low: 1.23, 95% CI: 0.62, 2.41; MexD score (tertiles) vs. elevated BP, OR, 95% CI; High: REF; Moderate: 0.53, 95% CI: 0.26, 1.07; Low: 0.91, 95% CI: 0.46, 1.79; Summary: Inverse: MeXD pattern (high vs. moderate) & reduced HDL cholesterol; NS/Null: aMED, DASH, HEI-2010, MeDS, MeXD & elevated TG, elevated BP; NS/Null: aMED, DASH, HEI-2010, MeDS & elevated TG, elevated BP; NS/Null: MeXD pattern (high vs. low) not associated with reduced HDL cholesterol | - Did not account for: None (all); - Dietary assessment: Single time point measurement of exposure; - Outcome measurement: Fasting lipid panel; - Study may not be powered to find the association; Single time dietary data assessment; - Funding: NIH/NHLBI
Satija, 2017^86^; United States; NHS, NHS II, HPFS; Analytic N=209,289; Participant characteristics:; - [underlined: Race and/or Ethnicity]: 97% NHW; - [underlined: SEP]: 100% Health professionals; - [underlined: Selection]: Excluded those with CVD (CHD, Stroke, CAD), cancer, or implausible dietary data.; - Current smoker: ~16.9%; - Mean BMI: 25.2 kg/m2; - Hypertension: 15.6% | - DP Age(s): NHS I: 30 to 55 y at baseline; Mean age: 50 y; - NHS II: 25 to 42 y at baseline; Mean age: 36.5 y; - HPFS: 40 to 75 y at baseline; Mean age: 53.5 y; - DP(s) examined: Plant Diet Index (PDI) [Satija, 2016]; - Healthful PDI (hPDI) [Satija, 2016]; - unhealthful PDI (uPDI) [Satija, 2016]; - DP Components: hPDI: Positive: Whole grains; Fruits; Vegetables; Nuts; Legumes; Vegetable oils; Tea/coffee; Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Negative: Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; - uPDI: Negative: Whole grains; Fruits; Vegetables; Nuts; Legumes; Vegetable oils; Tea/coffee; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; Positive: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; - PDI: Positive: Vegetables; Potatoes; Legumes; Fruit; Fruit Juices; Nuts; Whole Grains; Refined Grains; Tea and Coffee; Sugar-Sweetened and Artificially Sweetened Beverages; Sweets and Desserts; Negative: Fish or Seafood; Meat; Egg; Misc. Animal Foods; Dairy; Animal Fat; - DP Method(s): Index; Comparisons: Continuous (per-10-pt); Categorical, deciles of each DP | Follow-Up Duration: 23 y; PDI vs. CHD; NHS-I, Female, HR, 95% CI; D1: REF; D2: 1.02, 95% CI: 0.88, 1.18; D3: 1.04, 95% CI: 0.90, 1.21; D4: 0.97, 95% CI: 0.83, 1.13; D5: 1.01, 95% CI: 0.87, 1.18; D6: 0.88, 95% CI: 0.75, 1.03; D7: 0.97, 95% CI: 0.83, 1.13; D8: 0.92, 95% CI: 0.79, 1.09; D9: 0.95, 95% CI: 0.81, 1.12; D10: 0.87, 95% CI: 0.74, 1.03; Per-10: 0.92, 95% CI: 0.85, 0.98; P-trend: 0.04; NHS-II, Female, HR, 95% CI; D1: REF; D2: 0.95, 95% CI: 0.70, 1.29; D3: 0.91, 95% CI: 0.67, 1.24; D4: 0.95, 95% CI: 0.69, 1.29; D5: 0.80, 95% CI: 0.58, 1.12; D6: 0.89, 95% CI: 0.64, 1.23; D7: 0.71, 95% CI: 0.50, 1.01; D8: 0.66, 95% CI: 0.46, 0.95; D9: 0.80, 95% CI: 0.56, 1.13; D10: 0.77, 95% CI: 0.54, 1.11; Per-10: 0.81, 95% CI: 0.70, 0.95; P-trend: 0.02; HPFS, Men, HR, 95% CI; D1: REF; D2: 0.97, 95% CI: 0.85, 1.10; D3: 0.88, 95% CI: 0.77, 1.01; D4: 0.91, 95% CI: 0.80, 1.04; D5: 0.98, 95% CI: 0.86, 1.12; D6: 0.92, 95% CI: 0.81, 1.05; D7: 0.85, 95% CI: 0.74, 0.98; D8: 0.91, 95% CI: 0.80, 1.04; D9: 0.82, 95% CI: 0.71, 0.94; D10: 0.95, 95% CI: 0.83, 1.09; Per −10, HR: 0.96, 95% CI: 0.90, 1.01; P-trend: 0.10; NHS-I, NHS-II and HPFS - pooled results, HR, 95% CI; D1: REF; D2: 0.99, 95% CI: 0.91, 1.09; D3: 0.96, 95% CI: 0.87, 1.05; D4: 0.94, 95% CI: 0.86, 1.04; D5: 0.99, 95% CI: 0.90, 1.08; D6: 0.91, 95% CI: 0.83, 1.00; D7: 0.90, 95% CI: 0.82, 0.99; D8: 0.90, 95% CI: 0.82, 0.99; D9: 0.87, 95% CI: 0.79, 0.96; D10: 0.92, 95% CI: 0.83, 1.01; Per-10: 0.93, 95% CI: 0.90, 0.97; P-trend: 0.003; hPDI & CHD; NHS-I, Female, HR, 95% CI; D1: REF; D2: 0.91, 95% CI: 0.78, 1.06; D3: 0.90, 95% CI: 0.77, 1.05; D4: 0.88, 95% CI: 0.75, 1.02; D5: 0.87, 95% CI: 0.74, 1.01; D6: 0.83, 95% CI: 0.71, 0.97; D7: 0.76, 95% CI: 0.65, 0.90; D8: 0.83, 95% CI: 0.71, 0.98; D9: 0.78, 95% CI: 0.67, 0.92; D10: 0.68, 95% CI: 0.57, 0.80; Per-10 units: 0.86, 95% CI: 0.81, 0.91; P-trend<0.001; NHS-II, Female, HR, 95% CI; D1: REF; D2: 0.98, 95% CI: 0.71, 1.35; D3: 0.97, 95% CI: 0.71, 1.34; D4: 0.85, 95% CI: 0.60, 1.19; D5: 0.98, 95% CI: 0.71, 1.35; D6: 0.87, 95% CI: 0.62, 1.21; D7: 0.78, 95% CI: 0.55, 1.11; D8: 0.80, 95% CI: 0.57, 1.13; D9: 0.77, 95% CI: 0.54, 1.09; D10: 0.53, 95% CI: 0.36, 0.79; Per-10 units: 0.79, 95% CI: 0.69, 0.90; P-trend<0.001; HPFS, Men, HR, 95% CI; D1: REF; D2: 0.99, 95% CI: 0.87, 1.14; D3: 0.87, 95% CI: 0.76, 1.00; D4: 0.99, 95% CI: 0.86, 1.13; D5: 0.89, 95% CI: 0.78, 1.03; D6: 0.91, 95% CI: 0.79, 1.04; D7: 0.84, 95% CI: 0.73, 0.97; D8: 0.89, 95% CI: 0.77, 1.02; D9: 0.80, 95% CI: 0.70, 0.93; D10: 0.84, 95% CI: 0.73, 0.97; Per-10 units: 0.90, 95% CI: 0.86, 0.95; P-trend<0.001; NHS-I, NHS-II and HPFS - pooled results, HR, 95% CI; D1: REF; D2: 0.95, 95% CI: 0.86, 1.04; D3: 0.88, 95% CI: 0.80, 0.97; D4: 0.92, 95% CI: 0.84, 1.01; D5: 0.88, 95% CI: 0.80, 0.97; D6: 0.86, 95% CI: 0.78, 0.95; D7: 0.80, 95% CI: 0.73, 0.88; D8: 0.85, 95% CI: 0.77, 0.94; D9: 0.79, 95% CI: 0.71, 0.87; D10: 0.75, 95% CI: 0.68, 0.83; Per-10 units: 0.88, 95% CI: 0.85, 0.91; P-trend<0.001; uPDI & CHD; NHS-I, Female, HR, 95% CI; D1: REF; D2: 1.20, 95% CI: 1.02, 1.41; D3: 1.52, 95% CI: 1.30, 1.78; D4: 1.13, 95% CI: 0.96, 1.34; D5: 1.41, 95% CI: 1.20, 1.66; D6: 1.36, 95% CI: 1.16, 1.61; D7: 1.43, 95% CI: 1.21, 1.68; D8: 1.34, 95% CI: 1.13, 1.58; D9: 1.34, 95% CI: 1.13, 1.58; D10: 1.49, 95% CI: 1.26, 1.76; Per-10 units: 1.13, 95% CI: 1.06, 1.19; P-trend<0.001; NHS-II, Female, HR, 95% CI; D1: REF; D2: 1.67, 95% CI: 1.17, 2.38; D3: 1.45, 95% CI: 1.01, 2.10; D4: 1.56, 95% CI: 1.09, 2.25; D5: 1.29, 95% CI: 0.88, 1.89; D6: 1.59, 95% CI: 1.10, 2.30; D7: 1.46, 95% CI: 0.99, 2.14; D8: 1.91, 95% CI: 1.32, 2.75; D9: 1.37, 95% CI: 0.93, 2.03; D10: 1.77, 95% CI: 1.21, 2.59; Per-10 units: 1.16, 95% CI: 1.03, 1.31; P- trend: 0.04; HPFS, Male, HR, 95% CI; D1: REF; D2: 1.04, 95% CI: 0.92, 1.19; D3: 1.07, 95% CI: 0.94, 1.22; D4: 1.05, 95% CI: 0.91, 1.20; D5: 1.18, 95% CI: 1.04, 1.35; D6: 1.15, 95% CI: 1.01, 1.32; D7: 1.10, 95% CI: 0.96, 1.25; D8: 1.14, 95% CI: 0.99, 1.31; D9: 1.14, 95% CI: 0.99, 1.31; D10: 1.21, 95% CI: 1.05, 1.39; Per-10 units: 1.08, 95% CI: 1.03, 1.14; P-trend: 0.003; NHS-I, NHS-II and HPFS - pooled results, HR, 95% CI; D1: REF; D2: 1.14, 95% CI: 1.04, 1.25; D3: 1.24, 95% CI: 1.13, 1.37; D4: 1.12, 95% CI: 1.01, 1.23; D5: 1.26, 95% CI: 1.14, 1.39; D6: 1.25, 95% CI: 1.13, 1.37; D7: 1.25, 95% CI: 1.13, 1.38; D8: 1.23, 95% CI: 1.11, 1.36; D9: 1.21, 95% CI: 1.09, 1.34; D10: 1.32, 95% CI: 1.20, 1.46; Per-10 units: 1.10, 95% CI: 1.06, 1.14; P-trend<0.001; hPDI vs. CHD, HR, 95% CI; Age; <55 y: 0.59, 95% CI: 0.43, 0.82; P-trend: <0.001; ≥55 y: 0.76, 95% CI: 0.69, 0.85; P-trend: <0.001; BMI; <30 kg/m2: 0.72, 95% CI: 0.64, 0.80; P-trend: <0.001; ≥30 kg/m2: 0.84, 95% CI: 0.66, 1.05; P-trend: 0.05 uPDI vs. CHD, HR, 95% CI; Age; <55 y: 1.82, 95% CI: 1.33, 2.47; P-trend: 0.001; ≥55 y: 1.27, 95% CI: 1.14, 1.42; P-trend: <0.001; BMI; <30 kg/m2: 1.27, 95% CI: 1.13, 1.43; P-trend: <0.001; ≥30 kg/m2: 1.38, 95% CI: 1.11, 1.72; P-trend: 0.06; Summary: Inverse: PDI & CHD; Inverse: hPDI & CHD; hPDI & CHD, when stratified by age and BMI <30 kg/m2 & CHD; Positive: uPDI & CHD and when stratified by age and BMI; Null: hPDI & CHD for BMI ≥30 kg/m2 | - Did not account for: Race and/or ethnicity (mostly Whites); - Dietary assessment: Multiple exposure assessment; - Outcome measurement: CHD was non-fatal MI or fatal CHD; Medical record abstraction + probable cases; - CHD was non-fatal MI or fatal CHD. SES markers were adjusted for, but did not change the findings (although it was not part of the main model). Medical record abstraction and some probable cases included; - Funding: NIH/NCI, NIH/NHLBI
Schrauben, 2021^87^; United States; ARIC, CHS, MESA; Analytic N=27,271; Participant characteristics:; - [underlined: Race and/or Ethnicity]: 67.8% NHW, 23.8% Black, 5.5% Hispanic; - [underlined: SEP]: <High school: 23.3%; - High school/some college: 44.4%; - 4 yr degree or more: 32.3%; - [underlined: Selection]: Excluded participants with BMI<18.5 kg/m2. Included participants with serum creatinine measurement at baseline.; - Participants with CVD at baseline (i.e. with a history of heart failure, MI, coronary revascularization, stroke, transient ischemic attack or claudication) were included; - Hypertension: 44.7%; - Mean BMI: 27.7 kg/m2; BMI≥30: 27.2%; - Current smoker: 19.9% | - DP Age(s): 45 to 64 y at baseline, ARIC;; - >65 y at baseline, CHS;; - 45 to 84 y at baseline, MESA; - Mean age: 60.1 y; - DP(s) examined: Diet score (aligned with American Heart Association (AHA) component recommendations); - DP Components: Positive: Fruits and vegetables, fish, whole grains; Negative: sodium, sugar-sweetened beverages; Neutral/Moderate: Alcohol; - DP Method(s): Index; Comparisons: Categorical, Dichotomous | Follow-Up Duration: 16.7 y; Diet score vs. major coronary events, HR, 95% CI 0-1: REF; ≥2: 1.01, 95% CI: 0.95, 1.07; P-value: 0.86; Diet score vs. Ischemic stroke, HR, 95% CI; 0-1: REF; ≥2: 0.92, 95% CI: 0.83, 1.01; P-value: 0.08; Diet score vs. Heart failure, HR, 95% CI; 0-1: REF; ≥2: 0.99, 95% CI: 0.93, 1.05; P-value: 0.77; Summary: NS/Null: Diet score & major coronary events, ischemic stroke, heart failure | - Did not account for: Physical activity, Smoking; - Dietary assessment: Single time point measurement of exposure; - Outcome measurement: Adjudication; - Single time point measurement of diet; Unclear if FFQs were validated. Also, it is not clear if FFQ differed between cohorts, but cohort was controlled as a random effect; Participants with baseline CVD were included. Also, participants with CKD were included - so generalizability may be an issue; - Funding: NIH/NIDDK
Shah, 2018^88^; United States; Cooper Center Longitudinal Study; Analytic N=11,376; Participant characteristics:; - [underlined: Race and/or Ethnicity]: Predominantly NHW; - [underlined: SEP]: NR; - [underlined: Selection]: Excluded participants with missing data on covariates, prevalent CVD, discretionary fat intake>total fat, implausible energy intake, physical activity >140 metabolic equivalents. Participants who completed 3-day diet record were included; - Mean BMI: 25.8 kg/m2; - Current smoking: 11.9% | - DP Age(s): ≥20 y at baseline; Mean age at baseline: 47 y; - DP(s) examined: Mediterranean Diet Score (MDS) [Trichopolou, 2003]; - DASH Score [Fung, 2008]; - DP Components: MDS: Positive: Vegetables; Legumes; Fruit, Nuts; Cereals; Fish; MUFA/SFA. Negative score component: Red and Processed Meat; Dairy Products. Neutral: alcohol; - DASH: Positive: Vegetables; Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Added sugar; Sodium; - DP Method(s): Index; Comparisons: Continuous | Follow-Up Duration: 18.0 y; MDS vs. CVD mortality, HR, 95% CI 0.93, 95% CI: 0.85, 1.02; DASH Score vs. CVD mortality, HR, 95% CI 0.96, 95% CI: 0.86, 1.06; Summary: NS/Null: MDS, DASH scores & CVD mortality | - Did not account for: Race and/or ethnicity, SEP; - Dietary assessment: Single time point measurement of exposure; - Outcome measurement: National Death Index + ICD codes; - Sample from preventative medicine clinic may be less generalizable to those less likely to follow health prevention guidance. Single time point measurement of exposure.; - Funding: The Cooper Institute
Shams-White, 2022^89^; United States; NIH-AARP; Diet and Health Study; Analytic N=177,410; Participant characteristics:; - [underlined: Race and/or Ethnicity]: 93% NHW; - [underlined: SEP]: >50%: Had some college or college graduate; - [underlined: Selection]: Excluded if the questionnaire was completed by proxy, previous history of cancer, heart disease, cancer deaths not registry-confirmed, or if they reported extreme total energy intakes; Also excluded participants missing height and/or weight data, missing covariates, had extreme BMI or total minutes of moderate to vigorous physical activity; - Former or Current smoking: ~57.8%; - Mean BMI: 26.6 kg/m2 | - DP Age(s): 50 to 71 y at baseline; Mean age: 61.2 y; - DP(s) examined: WCRF/AICR Score - Diet Only [Romaguera 2012]; - DP Components: Positive: Vegetables and Fruit; Dietary Fiber. Negative: Red and Processed Meat; Sugary Drinks; Alcohol; Sodium; Energy-Dense Foods; - DP Method(s): Index; - Comparisons: Continuous, categorical WCRF/AICR scores vs. CVD mortality | Follow-Up Duration: 14.2 y; WCRF/AICR Score (continuous) vs. CVD mortality in male, HR, 95% CI, stratified by smoking; Never: 0.84, 95% CI: 0.77, 0.91; Former: 0.79, 95% CI: 0.75, 0.84; Current: 0.81, 95% CI: 0.71, 0.92; WCRF/AICR Score (continuous) vs. CVD mortality in female, HR, 95% CI, stratified by smoking; Never: 0.79, 95% CI: 0.73, 0.86; Former: 0.74, 95% CI: 0.68, 0.80; Current: 0.76, 95% CI: 0.67, 0.85; WCRF/AICR Score (categorical) vs. CVD mortality in male, HR, 95% CI, stratified by smoking; Never; 0-2: REF; >2 to <5: 0.51, 95% CI: 0.41, 0.63; 5-7: 0.51, 95% CI: 0.35, 0.73; Former; 0-2: REF; >2 to <5: 0.66, 95% CI: 0.57, 0.76; 5-7: 0.48, 95% CI: 0.34, 0.68; Current; 0-2: REF; >2 to <5: 0.67, 95% CI: 0.51, 0.87; 5-7: 0.44, 95% CI: 0.16, 1.21; WCRF/AICR Score (categorical) vs. CVD mortality in female, HR, 95% CI, stratified by smoking; Never; 0-2: REF; >2 to <5: 0.57, 95% CI: 0.45, 0.72; 5-7: 0.43, 95% CI: 0.30, 0.61; Former; 0-2: REF; >2 to <5: 0.55, 95% CI: 0.44, 0.70; 5-7: 0.27, 95% CI: 0.17, 0.42; Current; 0-2: REF; >2 to <5: 0.54, 95% CI: 0.40, 0.73; 5-7: 0.47, 95% CI: 0.26, 0.86; Summary: Inverse: WCRF/AICR score and CVD mortality among males, female who are never, former and current smokers; NS/Null: WCRF/AICR score and CVD mortality, current male smokers (5-7 category) | - Did not account for: None (all); - Dietary assessment: Single time point measurement of exposure; - Outcome measurement: SSA death file + National Death Index + SEER coding; - Single time point measure of exposure; - Funding: None
Shan, 2020^90^; United States; NHS, NHS II, HPFS; Analytic N=209,133; Participant characteristics:; - [underlined: Race and/or Ethnicity]: 97.7% NHW; - [underlined: SEP]: 100% Nurses and health professionals;; - [underlined: Selection]: Excluded participants who reported CVD, cancer, or diabetes at baseline, implausible energy intake; - Mean BMI: 24.9 kg/m2; - Smoker: ~53% | - DP Age(s): 30 to 55 y, age at baseline, NHS: Mean age: 50.2 y; - 25 to 42 y, age at baseline, NHS II; Mean age: 36.1 y; - 40 to 75 y, age at baseline, HPFS; Mean age: 53.2 y; - DP(s) examined: HEI-2015 (Healthy Eating Index-2015); AMED (Alternate Mediterranean Diet Score); HPDI (Healthful Plant-Based Diet Index); AHEI (Alternate Healthy Eating Index); - DP Components: HEI-2015: Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; PUFA+MUFA/SFA. Negative: Refined Grains; Added Sugars; SFA; Sodium; - AMED: Positive: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA/SFA. Negative: Red and Processed Meat. Neutral: Alcohol; - HPDI: Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Negative: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; - AHEI: Positive: Vegetables (not potatoes, French fries); Fruit; Nuts and Soy Protein; Cereal Fiber; White: Red Meat Ratio; PUFA: SFA; Multi-Vitamin Use. Negative: Trans-UFA. Neutral: Alcohol; - DP Method(s): Index; Comparisons: Categorical: quintiles of HEI-2015, AMED, HPDI, AHEI | Follow-Up Duration: up to 32 y; HEI-2015 (quintiles) vs. CVD, HR, 95% CI; Q1: REF; Q2: 0.93, 95% CI: 0.89, 0.97; Q3: 0.91, 95% CI: 0.87, 0.95; Q4: 0.86, 95% CI: 0.83, 0.90; Q5: 0.83, 95% CI: 0.79, 0.86; P-trend: <0.001; AMED (quintiles) vs. CVD, HR, 95% CI; Q1: REF; Q2: 0.94, 95% CI: 0.90, 0.98; Q3: 0.90, 95% CI: 0.87, 0.94; Q4: 0.88, 95% CI: 0.84, 0.92; Q5: 0.83, 95% CI: 0.79, 0.86; P-trend: <0.001; HPDI (quintiles) vs. CVD, HR, 95% CI; Q1: REF; Q2: 0.95, 95% CI: 0.91, 0.99; Q3: 0.91, 95% CI: 0.87, 0.95; Q4: 0.90, 95% CI: 0.86, 0.94; Q5: 0.86, 95% CI: 0.82, 0.89; p-trend: <0.001; AHEI (quintiles) vs. CVD, HR, 95% CI; Q1: REF; Q2: 0.91, 95% CI: 0.87, 0.95; Q3: 0.88, 95% CI: 0.85, 0.92; Q4: 0.84, 95% CI: 0.81, 0.88; Q5: 0.79, 95% CI: 0.75, 0.82; p-trend: <0.001; HEI-2015 (per 25-percentile increment) vs. CVD, HR:; 0.80, 95% CI: 0.77, 0.83; aMED (per 25-percentile increment) vs. CVD, HR:; 0.90; 95% CI: 0.87, 0.92; HPDI (per 25-percentile increment) vs. CVD, HR:; 0.86; 95% CI: 0.82, 0.89; AHEI (per 25-percentile increment) vs. CVD, HR:; 0.81; 95% CI: 0.78, 0.84; HEI-2015 (per 25-percentile increment) vs. CHD, HR:; 0.78, 95% CI: 0.74, 0.82; aMED (per 25-percentile increment) vs. CHD, HR:; 0.89; 95% CI: 0.86, 0.91; HPDI (per 25-percentile increment) vs. CHD, HR:; 0.84; 95% CI: 0.80, 0.87; AHEI (per 25-percentile increment) vs. CHD, HR:; 0.79; 95% CI: 0.76, 0.82; HEI-2015 (per 25-percentile increment) vs. stroke, HR:; 0.88, 95% CI: 0.81, 0.96; aMED (per 25-percentile increment) vs. stroke, HR:; 0.90; 95% CI: 0.86, 0.95; HPDI (per 25-percentile increment) vs. stroke, HR:; 0.92; 95% CI: 0.85, 1.00; AHEI (per 25-percentile increment) vs. stroke, HR:; 0.90; 95% CI: 0.83, 0.97; HEI-2015 vs. CVD, HR, 95% CI; NHW: 0.68, 95% CI: 0.64, 0.72; Minority racial/ethnic group (overall): 0.71, 95% CI:; 0.55, 0.91; NHB: 0.62, 95% CI: 0.33, 1.15; Hispanic: 0.48, 95% CI: 0.22, 1.07; Other: 0.77, 95% CI: 0.58, 1.03; AMED vs. CVD, HR, 95% CI; NHW: 0.80, 95% CI: 0.77, 0.84; Minority racial/ethnic group (overall): 0.79, 95% CI:; 0.68, 0.92; NHB: 0.86, 95% CI: 0.59, 1.27; Hispanic: 0.74, 95% CI: 0.46, 1.20; Other: 0.78, 95% CI: 0.66, 0.93; HPDI vs. CVD, HR, 95% CI; NHW: 0.78, 95% CI: 0.74, 0.83; Minority racial/ethnic group (overall): 0.70, 95% CI:; 0.55, 0.89; NHB: 0.76, 95% CI: 0.41, 1.40; Hispanic: 0.82, 95% CI: 0.40, 1.68; Other: 0.67, 95% CI: 0.51, 0.89; AHEI vs. CVD, HR, 95% CI; NHW: 0.70, 95% CI: 0.66, 0.74; Minority racial/ethnic group (overall): 0.72, 95% CI:; 0.58, 0.88; NHB: 0.78, 95% CI: 0.45, 1.34; Hispanic: 0.50, 95% CI: 0.26, 0.98; Other: 0.74, 95% CI: 0.58, 0.94; Summary: Inverse: HEI-2015, AMED, HPDI, AHEI & CVD risk; Inverse: HEI-2015, AMED, AHEI (per 25-percentile increment) and CVD, CHD, stroke; Inverse: HPDI (per 25-percentile increment) and CVD, CHD; Null: HPDI (per 25-percentile increment) & stroke; Inverse: HEI-2015 & CVD (White, minority racial/ethnic group - overall); NS/Null: HEI-2015 & CVD (Black, Hispanic, Other); Inverse: AMED & CVD (White, minority racial/ethnic group - overall, Other); NS/Null: HEI-2015 & CVD (Black, Hispanic); Inverse: HPDI vs. CVD (White, minority racial/ethnic group - overall, Other); NS/Null: Black, Hispanic; Inverse: AHEI & CVD (White, minority racial/ethnic group - overall, Other); NS/Null: Black, Hispanic | - Did not account for: None (all); - Dietary assessment: Multiple exposure assessment; - Outcome measurement: Medical record abstraction + some self-report (CABG) + National Death Index; - Findings may not be generalizable since most participants were health professionals and NHW; - Funding: NIH/NHLBI, NCI, NIDDK
Shan, 2023^91^; United States; NHS, HPFS; Analytic N=119,315; Participant characteristics:; - [underlined: Race and/or Ethnicity]:; 94.1% NHW; 1.2% Black; 0.8% Hispanic; 4.4% Others; - [underlined: SEP]: 100% Nurses, Health professionals; - [underlined: Selection]: Excluded participants with baseline CVD, cancer, or diabetes. Excluded participants who did not provide information on diet and those who had implausible energy intake; - Mean BMI: 25.2 k/m2; - Current & former smokers: 53.2% | - DP Age(s): 30 to 55 y at baseline, NHS; Mean age of women: 50.2 y; - 40 to 75 y at baseline, HPFS; Mean age of men: 53.3 y; - DP(s) examined: HEI-2015; AMED; HPDI; AHEI; - DP Components: HEI-2015: Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; PUFA+MUFA/SFA. Moderation: Refined Grains; Added Sugars; SFA; Sodium; - AMED: Vegetables, fruits, whole grains, nuts, legumes, fish, and ratio of monounsaturated fat to saturated fat; Negative: Red and processed meat, alcohol; - HPDI: Positive (Healthy Plant foods): whole grains, fruits, vegetables, nuts, legumes, vegetable oils, and tea and coffee; Negative (Less healthy plant foods): fruit juices, refined grains, potatoes, sugar-sweetened beverages, and sweets and desserts; Negative (Animal foods): animal fat including butter or lard, dairy, eggs, fish and seafood, meat, and miscellaneous animal-based foods; - AHEI-2010: Positive: Vegetables, whole fruit, whole grains, nuts and legumes, long-chain n-3 fats, polyunsaturated fatty acids; Negative: red and processed meat, trans fat, sodium, sugar-sweetened beverages and fruit juice; - DP Method(s): Index; Comparisons: Continuous, Healthy eating scores | Follow-Up Duration: up to 36 y; NHS and HPFS (pooled); CVD death, HR, 95% CI; HEI-2015: 0.87, 95% CI: 0.83, 0.92; AMED: 0.94, 95% CI: 0.91, 0.97; HPDI: 0.94, 95% CI: 0.89, 0.99; AHEI: 0.88, 95% CI: 0.84, 0.92; Heart disease death, HR, 95% CI; HEI-2015: 0.85, 95% CI: 0.80, 0.90; AMED: 0.94, 95% CI: 0.90, 0.97; HPDI: 0.92, 95% CI: 0.86, 0.97; AHEI: 0.85, 95% CI: 0.80, 0.90; Stroke death, HR, 95% CI; HEI-2015: 0.96, 95% CI: 0.86, 1.06; AMED: 0.95, 95% CI: 0.89, 1.02; HPDI: 1.02, 95% CI: 0.92, 1.14; AHEI: 0.96, 95% CI: 0.87, 1.06; NHS (female only); CVD death, HR, 95% CI; HEI-2015: 0.77, 95% CI: 0.72, 0.83; AMED: 0.86, 95% CI: 0.82, 0.91; HPDI: 0.85, 95% CI: 0.78, 0.92; AHEI: 0.77, 95% CI: 0.71, 0.83; Heart disease death, HR, 95% CI; HEI-2015: 0.74, 95% CI: 0.68, 0.81; AMED: 0.85, 95% CI: 0.80, 0.90; HPDI: 0.81, 95% CI: 0.74, 0.89; AHEI: 0.74, 95% CI: 0.68, 0.81; Stroke death, HR, 95% CI; HEI-2015: 0.85, 95% CI: 0.74, 0.98; AMED: 0.90, 95% CI: 0.82, 0.99; HPDI: 0.94, 95% CI: 0.81, 1.09; AHEI: 0.85, 95% CI: 0.74, 0.97; HPFS (male only); CVD death, HR, 95% CI; HEI-2015: 0.97, 95% CI: 0.90, 1.04; AMED: 1.00, 95% CI: 0.96, 1.05; HPDI: 1.02, 95% CI: 0.95, 1.10; AHEI: 0.97, 95% CI: 0.91, 1.04; Heart disease death, HR, 95% CI; HEI-2015: 0.94, 95% CI: 0.87, 1.02; AMED: 1.00, 95% CI: 0.95, 1.05; HPDI: 0.99, 95% CI: 0.92, 1.08; AHEI: 0.94, 95% CI: 0.87, 1.01; Stroke death, HR, 95% CI; HEI-2015: 1.11, 95% CI: 0.94, 1.31; AMED: 1.02, 95% CI: 0.92, 1.13; HPDI: 1.13, 95% CI: 0.96, 1.33; AHEI: 1.12, 95% CI: 0.97, 1.29; HEI-2015 vs. CVD death, HR, 95% CI (Pooled); Q1: REF; Q2: 0.97, 95% CI: 0.92, 1.03; Q3: 0.94, 95%; CI: 0.89, 1.00; Q4: 0.90, 95% CI: 0.85, 0.96; Q5: 0.89, 95% CI: 0.84, 0.94; p-trend: <0.001; HEI-2015 vs. Heart disease, HR, 95% CI (Pooled); Q1: REF; Q2: 0.97, 95% CI: 0.91, 1.04; Q3: 0.93, 95%; CI: 0.87, 1.00; Q4: 0.90, 95% CI: 0.84, 0.96; Q5: 0.86, 95% CI: 0.81, 0.92; p-trend: <0.001; HEI-2015 vs. Stroke, HR, 95% CI (Pooled); Q1: REF; Q2: 0.97, 95% CI: 0.86, 1.09; Q3: 0.97, 95% CI: 0.86, 1.10; Q4: 0.92, 95%; CI: 0.82, 1.04; Q5: 0.97, 95% CI: 0.86, 1.09; p-trend: 0.40; AMED vs. CVD death, HR, 95% CI (Pooled); Q1: REF; Q2: 0.97, 95% CI: 0.91, 1.02; Q3: 0.91, 95%; CI: 0.86, 0.96; Q4: 0.92, 95% CI: 0.87, 0.97; Q5: 0.91, 95% CI: 0.85, 0.96; p-trend: <0.001; AMED vs. Heart disease, HR, 95% CI (Pooled); Q1: REF; Q2: 0.97, 95% CI: 0.91, 1.03; Q3: 0.89, 95%; CI: 0.83, 0.95; Q4: 0.92, 95% CI: 0.86, 0.98; Q5: 0.90, 95% CI: 0.84, 0.96; P-trend: <0.001; AMED vs. Stroke, HR, 95% CI (Pooled); Q1: REF; Q2: 0.97, 95% CI: 0.86, 1.09; Q3: 0.9, 95%; CI: 0.84, 1.07; Q4: 0.91, 95% CI: 0.81, 1.03; Q5: 0.93, 95% CI: 0.82, 1.06; p-trend: 0.20; HPDI vs. CVD death, HR, 95% CI (Pooled); Q1: REF; Q2: 0.97, 95% CI: 0.92, 1.03; Q3: 0.95, 95%; CI: 0.90, 1.01; Q4: 0.96, 95% CI: 0.90, 1.01; Q5: 0.94, 95% CI: 0.88, 1.00; p-trend: 0.023; HPDI vs. Heart disease, HR, 95% CI (Pooled); Q1: REF; Q2: 0.98, 95% CI: 0.92, 1.05; Q3: 0.95, 95%; CI: 0.89, 1.01; Q4: 0.95, 95% CI: 0.88, 1.01; Q5: 0.93, 95% CI: 0.86, 0.99; p-trend: 0.004; HPDI vs. Stroke, HR, 95% CI (Pooled); Q1: REF; Q2: 0.94, 95% CI: 0.84, 1.06; Q3: 0.94, 95%; CI: 0.84, 1.06; Q4: 0.98, 95% CI: 0.87, 1.10; Q5: 0.97, 95% CI: 0.86, 1.10; p-trend: 0.68; AHEI vs. CVD death, HR, 95% CI (Pooled); Q1: REF; Q2: 1.02, 95% CI: 0.94, 1.10; Q3: 0.98, 95%; CI: 0.91, 1.06; Q4: 0.98, 95% CI: 0.90, 1.06; Q5: 0.98, 95% CI: 0.91, 1.07; P-value: 0.33; AHEI vs. Heart disease, HR, 95% CI (Pooled); Q1: REF; Q2: 0.98, 95% CI: 0.90, 1.07; Q3: 0.96, 95%; CI: 0.88, 1.04; Q4: 0.94, 95% CI: 0.86, 1.02; Q5: 0.94, 95% CI: 0.86, 1.03; P-value: 0.06; AHEI vs. Stroke, HR, 95% CI (Pooled); Q1: REF; Q2: 1.19, 95% CI: 0.98, 1.43; Q3: 1.09, 95%; CI: 0.91, 1.32; Q4: 1.17, 95% CI: 0.97, 1.41; Q5: 1.19, 95% CI: 0.98, 1.44; P-value: 0.13; Summary: Inverse: HEI-2015, AMED, HPDI and AHEI & risk of death from CVD, heart disease; NS/Null: HEI-2015, AMED, HPDI and AHEI and death from stroke | - Did not account for: None (all); - Dietary assessment: Multiple exposure assessment; - Outcome measurement: National Death Index + Medical records + adjudication; - Generalizability may be an issue since participants were predominantly White and were health professionals; - Funding: NR
Shikany, 2015^92^; United States; REGARDS; Analytic N=17,418; Participant characteristics:; - [underlined: Race and/or Ethnicity]: 62% White; 35% Black; - [underlined: SEP]: 8-25% with Income <20,000; 20-30% did not graduate high school;; - [underlined: Selection]: Excluded participants with IHD at baseline and missing FFQ; implausible energy intake; - Current smoker: 8-23%; - BMI: ~28 kg/m2 | - DP Age(s): ≥45 years; Mean age >65: 40-63%; - DP(s) examined: Convenience, Plant-based, Sweets/Fats, Southern, Alcohol/Salads; - DP Components: Convenience: Positive: Beans; Chinese food; Condiments; Desserts; Fish; Fried food; Fried potatoes; High fat dairy; Mexican dishes; Mixed dishes with meat; Organ meat; Pasta dishes; Pizza; Potatoes; Poultry; Processed meats; Red meat; Refined grains; Salty snacks; Shell fish; Soup; Sweet breakfast foods; Vegetables - green leafy; Vegetable mixed dishes; - Plant-based: Positive: 100% fruit juice; Beans; Bread - Whole Grain; Cereal; Cereal-high fiber; Fish; Fruit; Lowfat dairy; Milk alternatives; Milk - Lowfat; Poultry; Refined grains; Salad dressing/sauces; Seeds, nuts; Soup; Vegetable - cruciferous; Vegetable - dark yellow; Vegetable - green leafy; Vegetable - other; Vegetable - tomato; Vegetable mixed dishes; Water; Yogurt; Negative: Alcohol (Beer); Pizza; Soda; - Sweets/Fats: Positive: Added fats; Bread; Bread - Whole Grain; Butter; Candy; Chocolate; Coffee; Condiments; Desserts; Fried potatoes; Highfat dairy; Margarine; Milk - Highfat; Miscellaneous sugar; Pasta dishes; Pizza; Potatoes; Processed meats; Red meat; Refined grains; Salty snacks; Seeds, nuts; Sweet breakfast foods; Tea; - Southern: Positive: 100% fruit juice; Added fats; Bread; Egg and egg dishes; Fried food; Fried potatoes; Milk - Highfat; Miscellaneous sugar; Organ meat; Processed meats; Red meat; Refined grains; Shell fish; Soda; SSB Negative: Cereal-high fiber; Coffee; Lowfat dairy; Milk - Lowfat; Vegetable - green leafy; Yogurt; - Alcohol/salads: Positive: Added fats; Beer; Butter; Coffee; Eggs and egg dishes; Fish; Condiments; Highfat dairy; Liquor; Processed meats; Red meat; Salad dressing/sauces; Seeds, nuts; Shell fish; Vegetable - green leafy; Vegetable - tomato; Alcohol (Wine); Negative: 100% fruit juice; Cereal; Desserts; Sugar-sweetened beverages; Vegetable - dark yellow; Vegetable mixed dishes; - DP Method(s): Factor/Cluster; Comparisons: Categorical, quartiles of each DP | Follow-Up Duration: 5.8 y; Convenience & CHD, HR, 95% CI; Q1: REF; Q2: 1.04, 95% CI: 0.81, 1.33; Q3: 1.05, 95% CI: 0.82, 1.36; Q4: 0.95, 95% CI: 0.71, 1.27; p-trend: 0.85; Plant-based & CHD, HR, 95% CI; Q1: REF; Q2: 1.07, 95% CI: 0.84, 1.38; Q3: 1.06, 95% CI: 0.82, 1.37; Q4: 1.02, 95% CI: 0.76, 1.36; p-trend: 0.91; Sweets/Fats & CHD, HR, 95% CI; Q1: REF; Q2: 1.24, 95% CI: 0.95, 1.62; Q3: 1.28, 95% CI: 0.98, 1.69; Q4: 1.18, 95% CI: 0.86, 1.62; p-trend: 0.27; Southern & CHD, HR, 95% CI; Q1: REF; Q2: 1.04, 95% CI: 0.78, 1.40; Q3: 1.09, 95% CI: 0.82, 1.46; Q4: 1.37, 95% CI: 1.01, 1.85; p-trend: 0.036; Alcohol/Salads & CHD, HR, 95% CI; Q1: REF; Q2: 0.95, 95% CI: 0.74, 1.22; Q3: 0.98, 95% CI: 0.76, 1.27; Q4: 1.00, 95% CI: 0.76, 1.32; p-trend: 0.95; Summary: Positive: Southern & CHD; Null: Convenience & CHD; Null: Plant-based & CHD; Null: Sweets/Fats & CHD; Null: Alcohol/Salads & CHD | - Did not account for: None (all); - Dietary assessment: Single time point measurement of exposure; - Outcome measurement: IHD based on self-report or adjudicated by physician for MI event, cardiac enzymes, and/or ECG consistent with ischemia or MI; - IHD based on self-report or adjudicated by physician for MI event, cardiac enzymes, and/or ECG consistent with ischemia or MI until 2013; Single dietary intake assessment with FFQ.; - Funding: NINDS, NHLBI
Shikany, 2021^93^; United States; REGARDS; Analytic N=21,069; Participant characteristics:; - [underlined: Race and/or Ethnicity]: 33.2% Blacks; - [underlined: SEP]: 9.6% < high school; 15.7% <20,000/y; - [underlined: Selection]: Excluded participants other than Black or White, under active treatment for cancer, chronic medical conditions precluding long-term participation, cognitive impairment, current or impending residence in a nursing home or inability to communicate in English; - Current smoker: 13.6%; - BMI: 29.1 kg/m2; - Hypertension: 72%; - Dyslipidemia: 59.5%; - CHD at baseline: 17% | - DP Age(s): ≥45 y at baseline; Mean age: 64.9 y; - DP(s) examined: Mediterranean Diet Score (MDS) [Trichopolou 2003], Convenience, Plant-based, Sweets, Southern, Alcohol and Salad; - DP Components: Mediterranean Diet Score (MDS) [Trichopolou 2003]: Positive: Vegetables; Legumes; Fruit; Cereals; Fish; MUFA/SFA. Negative: Meat; Dairy Products. Neutral: Alcohol; - Convenience: High factor loading on mixed dishes, pasta dishes, pizza, Mexican food, and Chinese food; - Plant-based: High factor loading on vegetables, fruits, fruit juice, cereal, beans, fish, poultry, and yogurt; - Sweets: High factor loading on added sugars, desserts, chocolate, candy, and sweetened breakfast foods; - Southern: High factor loading on added fats, fried food, eggs and egg dishes, organ meats, processed meats, and sugar-sweetened beverages; - Alcohol and Salad: High factor loading on beer, wine, liquor, green leafy vegetables, tomatoes, and salad dressing; - DP Method(s): Index; Factor/Cluster; Comparisons: Categorical, Quartiles of each DP | Follow-Up Duration: 9.8 y; CVD mortality; Med Diet Score vs. Sudden cardiac death, HR, 95% CI; Group 1: REF; Group 2: 0.97, 95% CI: 0.76, 1.23; Group 3: 0.74, 95% CI: 0.55, 1.01; P-trend: 0.07; Convenience vs. Sudden cardiac death, HR, 95% CI; Q1: REF; Q2: 1.05, 95% CI: 0.77, 1.43; Q3: 1.14, 95% CI: 0.83, 1.57; Q4: 1.32, 95% CI: 0.93, 1.86; P-trend: 0.11; Plant-based vs. Sudden cardiac death, HR, 95% CI; Q1: REF; Q2: 1.16, 95% CI: 0.86,1.57; Q3: 1.01, 95% CI: 0.73,1.40; Q4: 1.19, 95% CI: 0.85,1.67; P-trend: 0.51; Sweets vs. Sudden cardiac death, HR, 95% CI; Q1: REF; Q2: 1.14, 95% CI: 0.85, 1.53; Q3: 0.83, 95% CI: 0.60, 1.16; Q4: 0.81, 95% CI: 0.56, 1.17; P-trend: 0.11; Southern vs. Sudden cardiac death, HR, 95% CI; Q1: REF; Q2: 1.18, 95% CI: 0.84, 1.66; Q3: 1.13, 95% CI: 0.80, 1.60; Q4: 1.46, 95% CI: 1.02, 2.10; P-trend: 0.06; Alcohol and salad vs. Sudden cardiac death, HR, 95% CI; Q1: REF; Q2: 1.02, 95% CI: 0.76, 1.38; Q3: 0.94, 95% CI: 0.69, 1.28; Q4: 0.94, 95% CI: 0.68, 1.30; P-trend: 0.61; Summary: NS/Null: Med diet score, Convenience, Plant-based, Sweets, Southern, Alcohol and salad DP & sudden cardiac death | - Did not account for: None (all); - Dietary assessment: Single time point measurement of exposure; - Outcome measurement: Medical records + adjudication; - FFQ (Block 98) not validated in REGARDS population and may be subject to measurement error; Single time point measurement of exposure; Difference between participants who completed the FFQ and those that did not; Findings may not be generalizable because the study only included Black and White participants; - Funding: NIH/NINDS
Shvetsov, 2016^94^; United States; Multiethnic Cohort Study; Analytic N=193,527; Participant characteristics:; - [underlined: Race and/or Ethnicity]: 24.6% White; 17.2% Black; 7.2% Native Hawaiian; 28.4% Japenese American; 22.7% Latino; - [underlined: SEP]: NR; - [underlined: Selection]: Excluded participants with prior history of cancer or heart disease at baseline and those missing demographic and other essential information. | - DP Age(s): 45 to 75 y at baseline; - DP(s) examined: Alternative Mediterranean Diet Score (aMED) [Fung, 2005]; - DP Components: Positive: Vegetables (not potatoes); Legumes; Fruit and 100% fruit juices; Nuts; Whole Grains; Fish; MUFA/SFA. Negative: Red and Processed Meat. Neutral: alcohol; - DP Method(s): Index; Comparisons: Continuous | Follow-Up Duration: 13-18 y; CVD mortality; aMED vs. CVD mortality, HR, 95% CI; Men; All races: 0.79, 95% CI: 0.74, 0.85; P-trend<0.05 White: 0.75, 95% CI: 0.66, 0.86; P-trend<0.05 African American: 0.77, 95% CI: 0.67, 0.89; P-trend<0.05; Native Hawaiian: 0.82, 95% CI: 0.65, 1.03; P-trend>0.05; Japanese American: 0.83, 95% CI: 0.73, 0.94; P-trend<0.05; Latino: 0.86, 95% CI: 0.75, 1.00; P-trend<0.05; Women; All races: 0.78, 95% CI: 0.72, 0.84; P-trend<0.05 White: 0.73, 95% CI: 0.62, 0.86; P-trend<0.05 African American: 0.76, 95% CI: 0.67, 0.87; P-trend<0.05; Native Hawaiian: 0.96, 95% CI: 0.74, 1.24; P-trend>0.05; Japanese American: 0.69, 95% CI: 0.59, 0.81; P-trend<0.05; Latino: 0.92, 95% CI: 0.77, 1.10; P-trend>0.05; Summary: Inverse: aMED & CVD mortality (men, all races); Inverse: aMED & CVD mortality (women, all races),; Inverse: aMED & CVD White (men & women), African American (men & women), Japanese American (men & women), Latino (men); Null: aMED & CVD mortality in Native Hawaiian (men & women), Latino (women) | - Did not account for: None (all); - Dietary assessment: Single time point measurement of exposure; - Outcome measurement: National Death Index + State files + SEER coding; - Funding: NIH, NCI
Song, 2023^95^; United States; NHANES; Analytic N=6887; Participant characteristics:; - [underlined: Race and/or Ethnicity]:; 55.3% NHW; 19.4% NHB; 18.5% Mexican American; 6.9% Other; - [underlined: SEP]: NR; - [underlined: Selection]: Excluded participants without data on the components of MIND diet, data on smoking status, mortality data, blood lipid levels; - ~70% participants had overweight/obesity; - 43% participants with hypertension; - ~72% with hyperlipidemia; - Current or former smokers: 48.8% | - DP Age(s): 20 to 85 y at baseline; Mean age: 47.1 y; - DP(s) examined: MIND diet score; - DP Components: MIND Diet Score: Positive: green leafy vegetables, other vegetables, nuts, berries, beans, whole grains, seafood, poultry, olive oil, and wine; Negative: red meats, butter, and stick margarine, cheese, pastries and sweets, and fried/fast food; - DP Method(s): Index; Comparisons: Categorical, based on cut-offs of MIND diet score | Follow-Up Duration: 10 y; CVD mortality; MIND diet score vs. CV mortality; MDS-L: REF; MDS-M: 0.82, 95% CI: 0.55, 1.18; MDS-H: 0.58, 95% CI: 0.42, 0.79; P-trend<0.001; Per-one score increase in MDS: 0.85, 95% CI: 0.77, 0.93; MIND diet score vs. CV mortality, only among those with hypertension; MDS-L: REF; MDS-M: 0.93, 95% CI: 0.67, 1.29; MDS-H: 0.62, 95% CI: 0.46, 0.85; P-trend: 0.001; Per-one score increase in MDS: 0.87, 95% CI: 0.79, 0.96; MIND diet score vs. CV mortality, only in those without hypertension; MDS-L: REF; MDS-M: 0.42, 95% CI: 0.17, 1.06; MDS-H: 0.47, 95% CI: 0.21, 1.07; P-trend: 0.096; Per-one score increase in MDS: 0.76, 95% CI: 0.58, 1.00; Summary: Inverse: MDS & CV mortality in the whole population and only those with hypertension; Null: MDS & CV mortality (without hypertension) | - Did not account for: SEP; - Dietary assessment: Single time point measurement of exposure; - Outcome measurement: National Death Index + ICD codes; - Funding: CAMS Innovation Fund for Medical Sciences (CIFMS)
Sotos-Prieto, 2015^96^; United States; NHS, HPFS; Analytic N=79,538; Participant characteristics:; - [underlined: Race and/or Ethnicity]: 96% White; - [underlined: SEP]: 100% Nurses and health professionals; - [underlined: Selection]: Excluded those with CVD, cancer, and missing/unreliable/impla usible dietary data.; - Current smoker: 15.9%; - Mean BMI: 25.2 kg/m2; - Hypertension: ~21%; - High cholesterol: ~25.7% | - DP Age(s): 40 to 75 y at baseline for HPFS; - 30 to 55 y at baseline for NHS; - Mean age: 56.4 y; - DP(s) examined: aMED (Alternate Med Diet Score) [Fung 2005]; - AHEI-2010 (Alternative Healthy Eating Index 2010) [Chiuve, 2012]; - DASH Score [Fung 2008]; - DP Components: aMED: Positive: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA/SFA. Negative: Red and Processed Meat. Neutral: Alcohol; - aHEI-2010: Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol; - DASH: Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Sodium; - DP Method(s): Index; Comparisons: Continuous, per SD; Categorical: quintiles (Q3, ref) | Follow-Up Duration: 20 y; AHEI-2010 vs. CVD, pooled, HR, 95% CI; Q1: 1.03, 95% CI: 0.96, 1.11; Q2: 1.05, 95% CI: 0.99, 1.11; Q3: REF; Q4: 0.98, 95% CI: 0.88, 1.10; Q5: 0.93, 95% CI: 0.88, 0.99; P-trend: 0.0003; Per 20% increase: 0.90, 95% CI: 0.85, 0.95; aMED vs. CVD, pooled, HR, 95% CI; Q1: 1.01, 95% CI: 0.95, 1.07; Q2: 0.95, 95% CI: 0.89, 1.00; Q3: REF; Q4: 0.97, 95% CI: 0.92, 1.03; Q5: 0.91, 95% CI: 0.86, 0.97; p-trend: 0.04; Per 20% increase: 0.97, 95% CI: 0.94, 0.99; DASH vs. CVD, pooled, HR, 95% CI; Q1: 1.08, 95% CI: 1.02, 1.15; Q2: 0.99, 95% CI: 0.94, 1.05; Q3: REF; Q4: 1.00, 95% CI: 0.94, 1.05; Q5: 0.99, 95% CI: 0.93, 1.05; P-trend: 0.21; Per 20% increase: 0.96, 95% CI: 0.89, 1.03; AHEI-2010 vs. CHD, pooled, HR, 95% CI; Q1: 1.06, 95% CI: 0.96, 1.13; Q2: 1.06, 95% CI: 0.99, 1.13; Q3: REF; Q4: 1.00, 95% CI: 0.94, 1.70; Q5: 0.92, 95% CI: 0.86, 0.99; P-trend <0.0001; Per 20% increase: 0.87, 95% CI: 0.82, 0.93; aMED vs. CHD, pooled, HR, 95% CI; Q1: 1.02, 95% CI: 0.95, 1.09; Q2: 0.94, 95% CI: 0.88, 1.00; Q3: REF; Q4: 0.97, 95% CI: 0.91, 1.03; Q5: 0.91, 95% CI: 0.85, 0.97; P-trend: 0.03; Per 20% increase: 0.97, 95% CI: 0.94, 0.99; DASH vs. CHD, pooled, HR, 95% CI; Q1: 1.11, 95% CI: 1.04, 1.19; Q2: 0.99, 95% CI: 0.93, 1.06; Q3: REF; Q4: 1.00, 95% CI: 0.94, 1.07; Q5: 0.99, 95% CI: 0.90, 1.09; P-trend: 0.21; Per 20% increase: 0.94, 95% CI: 0.86, 1.03; AHEI-2010 vs. Stroke, pooled, HR, 95% CI; Q1: 0.96, 95% CI: 0.86, 1.09; Q2: 1.05, 95% CI: 0.90, 1.22; Q3: REF; Q4: 0.94, 95% CI: 0.70, 1.26; Q5: 0.99, 95% CI: 0.80, 1.24; P-trend: 0.85; Per 20% increase: 1.02, 95% CI: 0.90, 1.15; aMED vs. Stroke, pooled, HR, 95% CI; Q1: 0.98, 95% CI: 0.85, 1.13; Q2: 0.99, 95% CI: 0.88, 1.11; Q3: REF; Q4: 0.97, 95% CI: 0.86, 1.09; Q5: 0.93, 95% CI: 0.82, 1.06; P-trend: 0.49; Per 20% increase: 0.99, 95% CI: 0.93, 1.05; DASH vs. Stroke, pooled, HR, 95% CI; Q1: 1.01, 95% CI: 0.87, 1.17; Q2: 1.00, 95% CI: 0.89, 1.13; Q3: REF; Q4: 0.99, 95% CI: 0.88, 1.12; Q5: 1.01, 95% CI: 0.89, 1.15; P-trend: 0.92; Per 20% increase, HR: 1.00, 95% CI: 0.92, 1.09; Summary: Inverse: AHEI-2010 & CVD, CHD; Inverse: AMED & CVD, CHD; NS/Null: DASH & CVD, CHD, stroke; NS/Null: AHEI & stroke; NS/Null: AMED & stroke | - Did not account for: SEP; - Dietary assessment: Multiple exposure assessment; - Outcome measurement: Medical records + probable + National Death Index; - Results per sex/cohort not extracted (only extracted pooled); Generalizability may be an issue since the study only included health professionals and nurses, who were majority white. Some “probable” cases were included in the outcome; - Funding: NIH
Sotos-Prieto, 2017^97^; United States; NHS, HPFS; Analytic N=73,739; Participant characteristics:; - [underlined: Race and/or Ethnicity]: 97% White; - [underlined: SEP]: 100% Nurses and health professionals; - [underlined: Selection]: Excluded those with a history of CVF, cancer at or before baseline, missing information on diet and lifestyle covariates, very low or high calorie intake; - Mean BMI: 25.1 kg/m2; - Current or former smoker: 55.8%; - Hypertension: 40.1%; - High cholesterol: 53.4% | - DP Age(s): 40 to 75 y at baseline, HPFS; - 30 to 55 y at baseline, NHS; - Mean age: ~63.7 y at baseline; - DP(s) examined: aMED (Alternate Med Diet Score) (Fung, 2005); - DASH Score (Fung, 2008); - AHEI (Alternative HEI) (Chiuve, 2012); - DP Components: aMED: Positive: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA/SFA. Negative: Red and Processed Meat. Neutral: alcohol; - DASH: Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened beverages; Sodium; - AHEI: Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: alcohol; - DP Method(s): Index; Comparisons: Continuous, Categorical: quintiles | Follow-Up Duration: 12 y; CVD mortality; aMED per 20 %tile increase, HR: 0.85, 95% CI: 0.76, 0.96; DASH per 20 %tile increase, HR: 0.93, 95% CI: 0.88, 0.99; AHEI per 20 %tile increase, HR: 0.96, 95% CI: 0.88, 1.05; Summary: Inverse: aMED, aHEI & CVD-mortality;; Null: DASH & CVD-mortality | - Did not account for: SEP; - Dietary assessment: Multiple exposure assessment; - Outcome measurement: National Death Index + Medical records + adjudication; - Generalizability may be an issue considering that most of the participants are White health professionals; - Funding: NIH
Steffen, 2014^98^; United States; CARDIA; Analytic N=4713; Participant characteristics:; - [underlined: Race and/or Ethnicity]: 50% White; 50% Black; - [underlined: SEP]: ~45-70% >high school; - [underlined: Selection]: Excluded participants with extreme caloric intake, participants being pregnant, MetS at baseline, lack of fasting blood sample; - Current smoking: 29.6%; - Mean BMI: ~24 kg/m2 | - DP Age(s): 18 to 30 y at baseline; Mean age at baseline: 24.9 y; - DP(s) examined: modified Mediterranean Diet pattern (mMedDiet) (Trichopoulou, 2003); - DP Components: mMedDiet: Positive: Whole grain products; fruit; vegetables; fruit+vegetable juice; legumes; nuts; poultry; fish; eggs; coffee and tea; MUFA+PUFA/SFA ratio; Negative: Red and processed meat; dairy products; fried vegetables; refined grain; sauces; snack foods (cake, cookies, pie, pastry, crackers, granola bars, snack chips, and popcorn); candy; sugar group (sugar, honey, syrup, jam&jelly, sweet sauces); sweetened beverages; diet beverages; Neutral: Alcohol; - DP Method(s): Index; Comparisons: Categorical: quintiles of mMedDiet | Follow-Up Duration: 25 y; mMedDiet vs incidence of elevated BP, %; Q1: 49.2; Q2: 38.8; Q3: 41.3; Q4: 44.6; Q5: 40.4; p-value: 0.10; mMedDiet vs incidence of high TG, %; Q1: 37.3; Q2: 27.9; Q3: 27.8; Q4: 29.9; Q5: 21.6; p-value: <0.001; mMedDiet vs incidence of low HDL-C, %; Q1: 68.4; Q2: 57.5; Q3: 56.4; Q4: 58.0; Q5: 59.3; p-value: 0.02; Summary: Inverse: mMedDiet and high TG, low HDL HDL-C; Null: mMedDiet and Elevated BP | - Did not account for: Physical activity, Anthropometry, Smoking; - Dietary assessment: Multiple exposure assessment; - Outcome measurement: Fasting lipid panel; - Only Whites and African Americans were included, so the findings may not be generalizable to the entire U.S. population; - Funding: NHLBI/NIH
Tharrey, 2018^99^; United States and Canada; Adventist Health Study-2; Analytic N=81,337; Participant characteristics:; - [underlined: Race and/or Ethnicity]: 26% Black; - [underlined: SEP]: ~18-25% ≤10,000; - 19-24% <High school; - [underlined: Selection]: Excluded those < 25 y, with self-reported CVD, implausible diet data, improbably/missing data, extreme BMI (<14, > 60); - Mean BMI: ~27 kg/m2; - Current or former smokers: ~18% | - DP Age(s): ≥ 25 y; Mean age: ~57 y; - DP(s) examined: n/a; - DP Components: “Grains”: higher for grains, other vegetables, potatoes and low for seafood, poultry, and yogurt; - “Processed Foods”: higher for cheese, animal fat, eggs, potatoes, milk, and low in soy; - “Meat”: higher for red meat, processed meat, poultry, seafood, and low in grains, yogurt, and soy; - “Legumes, Fruits & Vegetables”: higher for potatoes, vegetables, legumes, fruits, and low in milk; - “Nuts & Seeds”: higher for peanuts, treenuts and seeds, seafood, lower in eggs, and poultry; - DP Method(s): Factor/Cluster; Comparisons: Continuous, per 1pt; Categorical: quartiles | Follow-Up Duration: 9.4 y; CVD mortality; ‘Grains’ vs. CVD mortality, HR, 98.75% CI; Q1: REF; Q2: 0.91, 98.75% CI: 0.76, 1.08; Q3: 1.00, 98.75% CI: 0.80, 1.26; Q4: 0.86, 98.75% CI: 0.71, 1.03; Q5: 0.93, 98.75% CI: 0.76, 1.13; p-value: 0.303; ‘Processed Foods’ vs. CVD mortality, HR, 98.75% CI; Q1: REF; Q2: 1.01, 98.75% CI: 0.84, 1.22; Q3: 1.06, 98.75% CI: 0.88, 1.28; Q4: 1.15, 98.75% CI: 0.94, 1.40; Q5: 1.12, 98.75% CI: 0.90, 1.41; p-value: 0.073; ‘Meat’ vs. CVD mortality, HR, 98.75% CI; Q1: REF; Q2: 1.05, 98.75% CI: 0.73, 1.51; Q3: 1.06, 98.75% CI: 0.69, 1.64; Q4: 1.15, 98.75% CI: 0.80, 1.64; Q5: 1.46, 98.75% CI: 0.98, 2.18; p-value: 0.012; ‘Legumes, Fruits and Vegetables’ vs. CVD mortality, HR, 98.75% CI; Q1: REF; Q2: 0.92, 98.75% CI: 0.77, 1.10; Q3: 0.96, 98.75% CI: 0.80, 1.16; Q4: 0.99, 98.75% CI: 0.82, 1.20; Q5: 1.04, 98.75% CI: 0.84, 1.28; p-value: 0.56; ‘Nuts & Seeds’ vs. CVD mortality, HR, 98.75% CI; Q1: REF; Q2: 0.88, 98.75% CI: 0.64, 1.20; Q3: 0.84, 98.75% CI: 0.57, 1.22; Q4: 0.70, 98.75% CI: 0.49, 0.99; Q5: 0.56, 98.75% CI: 0.38, 0.81; p-value: <0.001; Summary: Inverse: ‘Nuts & Seeds’ & CVD mortality; Positive: ‘Meat’ & CVD mortality; Null: ‘Grains’, ‘Processed Foods’, or ‘Legume, Fruits and Vegetables’ & CVD mortality | - Did not account for: n/a; - Dietary assessment: Single time point measurement of exposure; - Outcome measurement: National Death Index + ICD codes; - Diet was assessed only at baseline; - Funding: AgroParisTech Foundation; NIH
Thomas, 2018^124^; United States; CARDIA; Analytic N=3890; Participant characteristics:; - [underlined: Race and/or Ethnicity]: 58% White 42% Black; - [underlined: SEP]: Education ~15 y; - [underlined: Selection]: Excluded participants without valid clinic BP measurements at baseline and at least 1 f/u examination. Also excluded those with self-reported use of antihypertensive medications, or a self-reported previous diagnosis of hypertension at baseline or missing covariate data. | - DP Age(s): 18 to 30 y at baseline; Mean age: 24.7 y; - DP(s) examined: DASH; - DP Components: DASH: Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Sodium; - DP Method(s): Index; - Comparisons: Continuous: per 4 unit higher score | Follow-Up Duration: 25.5 y; CVD intermediate: incident hypertension; DASH vs. incident hypertension, HR, 95% CI; Black: 0.91, 95% CI: 0.86, 0.98; White: 0.85, 95% CI: 0.79, 0.92; P-interaction: 0.17; DASH vs. incident hypertension, HR, 95% CI (stratified by SBP/DBP at baseline); <110/70: 0.89, 95% CI: 0.82, 0.96; 110 to 119/70 to 74: 0.86, 95% CI: 0.80, 0.94; 120 to 129/75 to 79: 0.90, 95% CI: 0.82, 0.99; P-interaction: 0.80; Summary: Inverse: DASH & incidence hypertension in Black and White; Inverse: DASH & incidence hypertension, when stratified by baseline SBP/DBP level | - Did not account for: None; - Dietary assessment: Single time point measurement of exposure; - Outcome measurement: Average of 2nd and 3rd reading was used for BP measurement; - Sodium intake data was unavailable. Unclear if TEI was accounted for.; - Funding: Northwestern University; NIH
Troeschel, 2021^100^; United States; REGARDS; Analytic N=17,465; Participant characteristics:; - [underlined: Race and/or Ethnicity]: 66.4% White 33.6% Black; - [underlined: SEP]: 93.6% had insurance; - 17.2% with income <$20,000/yr; - [underlined: Selection]: Excluded participants missing dietary data, alcohol data, physical activity data, smoking history data, waist circumference data, impausible waist circumference, sedentary data, social network data, lost to f/u. Also excluded participants with cancer diagnosis at baseline, kidney failure, BMI <18.5 and those with data anomalies; - Current smoker: 13.4%; - Mean BMI: 29.2 kg/m2 | - DP Age(s): ≥ 45 y at baseline; Mean age: 64.2 y; - DP(s) examined: Evolutionary-concordance lifestyle (ECL) dietary component; - DP Components: ECL: Positive: Vegetables, Fruits, Lean meats, Fish, Nuts, Fruit/vegetable diversity, calcium; Negative: Red/processed meats, Dairy products, Grains, Baked goods, SSB, Sodium; - DP Method(s): Index; Comparisons: Categorical: Quintiles of ECL | Follow-Up Duration: 10.3 y; CVD mortality; ECL vs. CVD mortality, HR, 95% CI; Q1: REF; Q2: 1.19, 95% CI: 0.99, 1.43; Q3: 1.19, 95% CI: 0.98, 1.44; Q4: 1.11, 95% CI: 0.91, 1.34; Q5: 1.07, 95% CI: 0.86, 1.32; p-trend: 0.76; Summary: NS/Null: Evolutionary-concordance diet score & CVD mortality | - Did not account for: None (all); - Dietary assessment: Single time point measurement of exposure; - Outcome measurement: SSA death file + National Death Index + adjudication; - A number of participants were excluded because of exposure missigness. The findings may not be generalizable since the study oversampled participants from the stroke belt; Single time point assessment; - Funding: NIH/NINDS, NIA, NHLBI; Anne and Wilson Franklin Foundation
Tsivgoulis, 2015^101^; United States; REGARDS; Analytic N=20,197; Participant characteristics:; - [underlined: Race and/or Ethnicity]: 33% Black; - [underlined: SEP]: 14-22% Income >$75,000; - 29-48% college graduates; - [underlined: Selection]: Excluded participants with a history of stroke, incomplete dietary data, missing follow-up. All at high-risk of stroke; - Heart disease: ~16%; - Hypertension: 48%; - Obesity: 36%; - Current smoking: ~13.4% | - DP Age(s): ≥ 45 y at baseline; Mean age: 65 y; - DP(s) examined: Mediterranean Diet Score (MDS) [Trichopolou 2003]; - DP Components: MDS (MeD): Positive: Vegetables; Legumes; Fruit; Cereals; Fish; MUFA/SFA. Negative: Red and Processed Meat; Dairy Products. Neutral: Alcohol; - DP Method(s): Index; Comparisons: Categorical, low (ref; 0-3), average (4-5), high (6-9); median split (low, high) | Follow-Up Duration: 6.5 y; Med Diet Score vs. ischemic stroke, HR, 95% CI; High: REF; Average: 1.24, 95% CI: 0.98, 1.59; p-value: 0.079; Low: 1.29, 95% CI: 0.99, 1.67; p-value: 0.057; Med Diet Score (dichotomous) vs. ischemic stroke, HR, 95% CI; High (5-9): REF; Low (0-4): 1.27, 95% CI: 1.04, 1.54; p-value: 0.0164; Med Diet Score vs. hemorrhagic stroke, HR, 95% CI; High: REF; Average: 0.84, 95%CI: 0.49, 1.46; p-value: 0.53; Low: 0.64, 95% CI: 0.34, 1.21, p-value: 0.16; Med Diet Score vs. hemorrhagic stroke, HR, 95% CI; High (5-9): REF; Low (1-4): 0.93, 95% CI: 0.57, 1.51; p-value: 0.76; Summary: Inverse: MDS & Ischemic stroke;; Null: MDS & hemorrhagic stroke | - Did not account for: None (all); - Dietary assessment: Single time point measurement of exposure; - Outcome measurement: Medical record abstraction + adjudication; - Exposure assessment only at one time point (baseline); The study findings may not be generalizable since the study only included Black and White participants; - Funding: NINDS/NIH
Wang P, 2023^104^; United States; NHS, NHS II, HPFS; Analytic N=205,852; Participant characteristics:; - [underlined: Race and/or Ethnicity]: Predominantly Whites (based on previous studies in this cohort); - [underlined: SEP]: 100% Nurses and health professionals; - [underlined: Selection]: Excluded participants missing DP scores, implausible energy intake, with a baseline history of CVD, diabetes, cancer and extreme BMI.; - Mean BMI: ~25 kg/m2; - Current smoking: 18.9% | - DP Age(s): 30 to 55 y at baseline, NHS;; - 25 to 42 y at baseline, NHS II;; - 40 to 75 y at baseline, HPFS; - Mean age: 55.3 y; - DP(s) examined: AHEI-2010; AMED [Fung, 2005]; hPDI; DASH; Diabetes Risk Reduction Diet (DRRD); WCRF; rEDIH; rEDIP; - DP Components: AHEI-2010: Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol; - aMED: Positive: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA/SFA. Negative: Red and Processed Meat. Neutral: Alcohol; - hPDI: Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Negative: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; - DASH: Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low fat dairy; Negative: Red and Processed Meat; Sweetened beverages; Sodium;; - DRRD: Positive: Fruit, Cereal Fiber, Nuts, Coffee, PUFA/SFA; Negative: Red meat, SSB and fruit juices, Trans Fat, Glycemic Index; - WCRF: Positive: Vegetables and Fruit; Dietary Fiber. Negative: Red and Processed Meat; Sugary Drinks; Alcohol; Sodium; Energy-Dense Foods; - EDIH: Positive: Processed meat, potatoes, low energy carbonated drinks and eggs; Inverse: Beer, wine, coffee, snacks, fruit juice, nuts, sweets desserts, oil and vinegar salad dressing, and mayonnaise and other creamy salad dressings; - EDIR: Positive: Processed meat, red meat, potatoes, low energy carbonated drinks, margarine and eggs; Inverse: Dark yellow vegetables, leafy green vegetables, beer, wine, liquor, coffee, oil and vinegar salad dressing, pizza, sweets desserts, snacks, condiments and fruit juice; - DP Method(s): Index; Comparisons: Categorical (90th vs. 10th percentile) | Follow-Up Duration: up to 32 y; AHEI-2010 and:; Major CVD + SES, HR: 0.79, 95% CI: 0.75, 0.83; Major CVD + BMI, HR: 0.79, 95% CI: 0.75, 0.83; CHD, + SES, HR: 0.75, 95% CI: 0.70, 0.80; CHD, + BMI, HR: 0.75, 95% CI: 0.71, 0.80; Stroke, + SES, HR: 0.86, 95% CI: 0.79, 0.93; Stroke, + BMI, HR: 0.86, 95% CI: 0.79, 0.93; Major CVD without alcohol, HR: 0.82, 95% CI: 0.78, 0.86; AMED and:; Major CVD + SES, HR: 0.82, 95% CI: 0.78, 0.86; Major CVD + BMI, HR: 0.83, 95% CI: 0.79, 0.87; CHD + SES, HR: 0.80, 95% CI: 0.75, 0.85; CHD, + BMI, HR: 0.81, 95% CI: 0.76, 0.87; Stroke + SES, HR: 0.85, 95% CI: 0.79, 0.92; Stroke + BMI, HR: 0.86, 95% CI: 0.79, 0.93; Major CVD without alcohol, HR: 0.83, 95% CI: 0.79, 0.87; hPDI and:; Major CVD, + SES, HR: 0.84, 95% CI: 0.80, 0.88; Major CVD + BMI, HR: 0.85, 95% CI: 0.81, 0.90; CHD + SES, HR: 0.80, 95% CI: 0.76, 0.86; CHD + BMI, HR: 0.82, 95% CI: 0.76, 0.87; Stroke + SES, HR: 0.92, 95% CI: 0.85, 0.99; Stroke + BMI, HR: 0.92, 95% CI: 0.86, 1.00; DASH and:; Major CVD, + SES, HR: 0.83, 95% CI: 0.79, 0.87; Major CVD, + BMI, HR: 0.83, 95% CI: 0.79, 0.87; CHD, + SES, HR: 0.81, 95% CI: 0.76, 0.87; CHD, + BMI, HR: 0.81, 95% CI: 0.76, 0.87; Stroke, + SES, HR: 0.86, 95% CI: 0.79, 0.93; Stroke, + BMI, HR: 0.86, 95% CI: 0.79, 0.93; DRRD and:; Major CVD, + SES, HR: 0.74, 95% CI: 0.71, 0.78; Major CVD + BMI, HR: 0.75, 95% CI: 0.71, 0.79; CHD, + SES, HR: 0.73, 95% CI: 0.69, 0.78; CHD, + BMI 0.74, 95% CI: 0.69, 0.79; Stroke, + SES, HR: 0.77, 95% CI: 0.71, 0.83; Stroke, + BMI, HR: 0.77, 95% CI: 0.71, 0.83; WCRF/AICR and :; Major CVD, + SES, HR: 1.01, 95% CI: 0.96, 1.06; Major CVD, + BMI, HR: 0.99, 95% CI: 0.94, 1.03; CHD, + SES, HR: 1.01, 95% CI: 0.95, 1.07; CHD, + BMI, HR: 0.98, 95% CI: 0.92, 1.04; Stroke, + SES, HR: 1.03, 95% CI: 0.96, 1.11; Stroke, + BMI, HR: 1.01, 95% CI: 0.94, 1.09; Major CVD, HR, 95% CI 0.88, 95% CI: 0.84, 0.92; rEDIH and:; Major CVD, + SES (Reverse scored), HR: 0.70, 95%; CI: 0.66, 0.73; Major CVD, + BMI 0.76, 95% CI: 0.72, 0.79; CHD, + SES, HR: 0.65, 95% CI: 0.61, 0.69; CHD, + BMI, HR: 0.71, 95% CI: 0.67, 0.76; Stroke, + SES, HR: 0.77, 95% CI: 0.72, 0.83; Stroke, + BMI, HR: 0.82, 95% CI: 0.77, 0.89; Major CVD, HR, 95% CI, without alcohol 0.72, 95%; CI: 0.68, 0.75; rEDIP and:; Major CVD,+ SES (Reverse scored), HR: 0.70, 95%; CI: 0.67, 0.73; Major CVD, + BMI, HR: 0.75, 95% CI: 0.72, 0.79; CHD, + SES, HR: 0.66, 95% CI: 0.62, 0.69; CHD, + BMI, HR: 0.71, 95% CI: 0.67, 0.75; Stroke, + SES, HR: 0.77, 95% CI: 0.72, 0.83; Stroke, + BMI, HR: 0.82, 95% CI: 0.76, 0.88; Major CVD without alcohol, HR: 0.73, 95% CI: 0.70, 0.76; Summary: Inverse: AHEI-2010 & major CVD, CHD, stroke; Inverse: AMED & major CVD, CHD, stroke; Inverse: hPDI & major CVD, CHD, stroke (only when adjusted for SES); Inverse: DASH & major CVD, CHD, stroke; Inverse: DRRD & major CVD, CHD, stroke; Inverse: rEDIH & major CVD, CHD, stroke; Inverse: rEDIP & major CVD, CHD, stroke; Null: WCRF/AICR & major CVD, CHD, stroke | - Did not account for: None (all); - Dietary assessment: Multiple exposure assessment; - Outcome measurement: Medical record abstraction + National Death Index; - Predominantly White and health professionals, so the findings may not be entirely generalizable; - Funding: CDC
Wang, 2020^103^; United States; Study of Women’s Health Across the Nation (SWAN); Analytic N=1246; Participant characteristics:; - [underlined: Race and/or Ethnicity]: 52.8% NHW, 28.6% African American, 12.7% Chinese, 5.9% Hispanic; - [underlined: SEP]: 48.7% College, post-college; 30.3% Some college; 21% High school or less;; - 32.3% some what or very hard to pay for basics; - [underlined: Selection]: Excluded participants with incomplete data on 3 specific measures of carotid atherosclerosis, not having high quality dietary data implausible energy intake, self-reported MI, angina, stroke at baseline or before carotid scans; missing major covariates; - Current or former smokers: 37.8%; - Elevated BP: 26.5%; - Elevated TG: 17.4%; - Abdominal obesity: 39% | - DP Age(s): 42 to 52 y: Mean age at 46.3 y at baseline and 60.2 y at follow-up; - DP(s) examined: PCA-Western, PCA-Prudent, RRR-Western, PLS-Western; - DP Components: PCA-Western: High: Dairy products, Pizza, Unprocessed red meat, Processed red meat, Salad dressings; Low: Fruits, Milk with lower fat content, Legumes, Cruciferous vegetables, Tomatoes; - PCA-PrudentL: High: Dark-yellow vegetables, Green leafy vegetables, Cruciferous vegetables, Legumes, Fruits; Low: Whole milk, Margarine, Sweets and desserts, Organ meat, Beer; - RRR-Western: High: Margarine, Fried fish, Artifically sweetened beverages, Processed red meat, Sugar-sweetened beverages; Low: Soup, Fiber cereals, Fruits, Cruciferous vegetables, Wine; - PLS-Western: High: French fries, Processed red meat, Fried fish, Margarine, Sugar-Sweetened beverages; Low: Fruits, Legumes, Dark-yellow vegetables, Cruciferous vegetables, Soup; - DP Method(s): Factor/Cluster; RRR; Comparisons: Categorical: Quartiles of dietary patterns | Follow-Up Duration: 22 y; PCA-Western vs. Carotid plaques, RR, 95% CI; Q1: REF; Q2: 0.87, 95% CI: 0.65, 1.15; Q3: 0.85, 95% CI: 0.61, 1.17; Q4: 0.79, 95% CI: 0.53, 1.17; P-trend: 0.35; PCA-Prudent; Q1: REF; Q2: 1.14, 95% CI: 0.88, 1.47; Q3: 1.02, 95% CI: 0.77, 1.35; Q4: 1.09, 95% CI: 0.82, 1.50; p-trend: 0.74; RRR-Western; Q1: REF; Q2: 0.77, 95% CI: 0.56, 1.05; Q3: 0.86, 95% CI: 0.63, 1.18; Q4: 1.01, 95% CI: 0.75, 1.35; PLS-Western; Q1: REF; Q2: 1.17, 95% CI: 0.86, 1.58; Q3: 1.06, 95% CI: 0.78, 1.46; Q4: 1.10, 95% CI: 0.80, 1.51; P-trend: 0.66; Summary: NS/Null: PCA-Western, PCA-Prudent, RRR-Western, PLS-Western & Carotid plaques | - Did not account for: None (all); - Dietary assessment: Multiple exposure assessment; - Outcome measurement: Carotid ultrasound images; - Outcome measured only once and it is unclear if carotid plaques could be attributed to the diet; The study conducted multiple statistical testing; - Funding: NIH/NIA, NINR, ORWH, NIA
Wang, 2021^102^; United States; PLCO (Prostate, Lung, Colorectal, and Ovarian Cancer Screening Trial); Analytic N=86,633; Participant characteristics:; - [underlined: Race and/or Ethnicity]: ~91% NHW; 2-5% NHB; ~1% Hispanic; - [underlined: SEP]: 37% college graduates; - [underlined: Selection]: Excluded participants without baseline questionnaire, failed to complete diet history questionnaire, invalid diet health questionnaire, diagnosis of cancer, stroke, heart attack, diabetes before completing the questionnaire; - Mean BMI: 26.9 kg/m2; - Current or former smokers: 50.7%; - History of hypertension: 28.9% | - DP Age(s): 55 to 74 y at baseline, Mean age: ~65 y; - DP(s) examined: Dietary diabetes risk-reduction score; - DP Components: Positive: cereal fiber (insoluble fiber), ratio of polyunsaturated to saturated fatty acids, coffee, and nuts; Negative: glycemic index, trans-fatty acids, red and processed meat, and sugar-sweetened beverages (soft drinks or fruit drinks); - DP Method(s): Index; Comparisons: Categorical: Quintiles of dietary diab risk-reduction score | Follow-Up Duration: 13.6 y; Dietary diabetes risk-reduction score vs. CVD mortality; Q1: REF; Q2: 0.85, 95% CI: 0.78, 0.92; Q3: 0.80, 95% CI: 0.73, 0.88; Q4: 0.82, 95% CI: 0.75, 0.90; Q5: 0.69, 95% CI: 0.62, 0.76; P-trend: <0.001; Summary: Inverse: Dietary diabetes risk score & CVD mortality | - Did not account for: None (all); - Dietary assessment: Single time point measurement of exposure; - Outcome measurement: National Death Index + ICD codes; - Diet was meaasured only at baseline; Outcome assessment may have been subject to misclassification; Participants were predominantly White, so generalizability may be an issue; - Funding: NCI/NIH
Wang, 2022^105^; United States; NHANES; Analytic N=40,074; Participant characteristics:; - [underlined: Race and/or Ethnicity]:; ~48.2% non-Hispanic White; ~18.5% Mexican American; ~20.2% non-Hispanic Black; ~6.8% Other Hispanic; ~6.2% Other race; - [underlined: SEP]: ~21-32% ≤ 12th grade; ~23-25% High school/GED/equivalent; ~43-55% more than high school; - ~23-31% <1.30; ~32-35% 1.3-3.49; ~25-36.8% ≥3.50; - [underlined: Selection]: Excluded participants with implausible energy intake or without linked mortality data; - Mean BMI: 28.6 kg/m2; - Current or former smoker: 50.8% | - DP Age(s): 18 to 85 y at baseline; Mean age: 47.3 y; - DP(s) examined: Empirically dietary indices for hyperinsulinaemia (EDIH) and empirically dietary indices for insulin resistance (EDIR); - DP Components: EDIH: Positive: Processed meat, potatoes, low energy carbonated drinks and eggs; Inverse: Beer, wine, coffee, snacks, fruit juice, nuts, sweets desserts, oil and vinegar salad dressing, and mayonnaise and other creamy salad dressings; - EDIR: Positive: Processed meat, red meat, potatoes, low energy carbonated drinks, margarine and eggs; Inverse: Dark yellow vegetables, leafy green vegetables, beer, wine, liquor, coffee, oil and vinegar salad dressing, pizza, sweets desserts, snacks, condiments and fruit juice; - DP Method(s): RRR; Comparisons: Categorical: Quintiles of EDIH and EDIR | Follow-Up Duration: 7.8 y; CVD mortality; EDIH vs. CVD mortality, HR, 95% CI; Q1: REF; Q2: 1.04, 95% CI: 0.84, 1.29; Q3: 1.29, 95% CI: 1.04, 1.59; Q4: 1.01, 95% CI: 0.81, 1.27; Q5: 1.41, 95% CI: 1.15, 1.74; Per 1-SD: 1.11, 95% CI: 1.04, 1.20; p-trend: 0.002; EDIR vs. CVD mortality, HR, 95% CI; Q1: REF; Q2: 1.16, 95% CI: 0.94, 1.43; Q3: 1.25, 95% CI: 1.01, 1.55; Q4: 1.23, 95% CI: 0.99, 1.53; Q5: 1.35, 95% CI: 1.09, 1.67; Per 1-SD: 1.11, 95% CI: 1.04, 1.20; p-trend: 0.005; Summary: Positive: EDIH, EDIR & CVD mortality | - Did not account for: Alcohol; Anthropometry; - Dietary assessment: Single time point measurement of exposure; - Outcome measurement: National Death Index + ICD codes; - Alcohol and anthropometry not adjusted for. Further adjustment for BMI and DM status in sensitivity analyses attenuated findings but they still remained. Not sure how comparable this is with other DPs. Single time point measure; - Funding: National Natural Science Foundation of China, Anhui Provincial Natural Science Foundation, Anhui Provincial Education Department, Anhui Medical University
Wang, 2023^106^; United States; NHANES; Analytic N=23,212; Participant characteristics:; - [underlined: Race and/or Ethnicity]: NHW: 67.6%; Non-Hispanic Black: 9.6%; Mexian American: 9.9%; Other Hispanic: 5.0%; Other race: 7.9%; - [underlined: SEP]: 16.7 < High school; 22.8% high school; 60.5% college graduate or above; - Family Poverty Income Ratio (PIR): 3.0; - [underlined: Selection]: Excluded participants with missing dietary questionnaires, sleep questionnaire and aged =<18y, or lost to f/u; - 28.8 kg/m2 BMI; - 40.1% Hypertension; - 45.7% Smoking | - DP Age(s): ≥ 45 y at baseline; Mean age: 46.6 y; - DP(s) examined: aMED [Fung, 2005]; - DP Components: aMED: Positive: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA/SFA. Negative: Red and Processed Meat. Neutral: Alcohol; - DP Method(s): Index; Comparisons: Continuous, Categorical (Below median vs. median vs above median) | Follow-Up Duration: 9.3 y; CVD mortality; aMED vs. CVD Mortality, HR, 95% CI; Higher aMED: REF; Median aMED: 1.05, 95% CI: 0.94, 1.50, P-value: 0.10; Low aMED: 1.13, 95% CI: 1.05, 1.51, P-value: 0.04; aMED (continuous) vs. CVD mortality, HR, 95% CI 0.99, 95% CI: 0.85, 1.15, P-value: 0.90; Summary: Inverse: aMED (higher vs. lower) & CVD mortality; Null: aMED (continuous) & CVD mortality | - Did not account for: Physical activity; - Dietary assessment: Two consecutive 24 hr recalls; - Outcome measurement: National Death Index + ICD codes; - Two 24 hr recalls close in time; - Funding: None
Weng, 2013^107^; United States; ARIC Study; Analytic N=9913; Participant characteristics:; - [underlined: Race and/or Ethnicity]: 18% Black; - [underlined: SEP]: Education: 19% < high-school; - [underlined: Selection]: Excluded those with missing data, implausble TEI, or HTN or high-BP at baseline, and who were not white or “African-American”; - Current smoking: ~27.1% | - DP Age(s): 45 to 64 y at baseline; Mean age: ~53.5 y; - DP(s) examined: Healthy Food Score (HFS) [Steffen 2005]; - DP Components: HFS, Positive: Vegetables; Fruit (without juice); Fruit juice; Legumes; Nuts; Whole Grains; Refined grain; Dairy (combined low-fat and high fat milk, cheese, yogurt, ice cream); Fish; Coffee and tea; Negative: Meat (combined poultry, processed meat, beef, pork, and lamb); Diet beverages; Sugar-sweetened beverages; Neutral: alcohol; - DP Method(s): Index; Comparisons: Categorical and linear trend of HFS quintiles (Q1, HR: 1 REF) | Follow-Up Duration: ~9 y; HFS & “High BP”, HR, 95% CI; Q1: REF; Q2: 1.04, 95% CI: 0.88, 1.22; Q3: 1.11, 95% CI: 0.94, 1.31; Q4: 1.03, 95% CI: 0.87, 1.23; Q5: 1.08, 95% CI: 0.91, 1.29; p-trend: 0.90; HFS & Hypertension, HR, 95% CI; Q1: REF; Q2: 0.98, 95% CI: 0.88, 1.10; Q3: 0.92, 95% CI: 0.82, 1.04; Q4: 0.92, 95% CI: 0.81, 1.05; Q5: 0.90, 95% CI: 0.79, 1.02; P-trend: 0.06; Summary: NS/Inverse: HFS & hypertension; NS: HFS & high-BP | - Did not account for: None (all); - Dietary assessment: Multiple exposure assessment; - Outcome measurement: Multiple measures of BP; - High BP defined as SBP/DBP=120-139/90+ mmHg and not on anti-HTN-meds; HTN defined as SBP/DBP ≥40/≥90 mmHg or taking anti-HTN meds;; - High-BP incident cases, n=1663; HTN incident cases, n=2853;; - FFQ twice at baseline and exam 3;; - Conducted partial component analyses for HFS without meat, dairy, nuts, or those combined (without meat,dairy,nuts); - Funding: NIH
Weston, 2022^108^; United States; Jackson Heart Study (JHS); Analytic N=3635; Participant characteristics:; - [underlined: Race and/or Ethnicity]: 100% African Americans; - [underlined: SEP]: ~15 < High school; 17-21% High school; ~63-69% attended college or trade school (stratified by tertiles of overall PDI); - [underlined: Selection]: Excluded participants if they had CVD, MI or stroke at baseline, did not complete the FFQ, or implausible/unavailable dietary data, missing covariate data.; - Current or former smokers: 28.8%; - Hypertension: 52.4%; - Mean BMI: 31.7 kg/m2 | - DP Age(s): 21 to 95 y at baseline; Mean age: 53.9 y; - DP(s) examined: Plant-based diet index (PDI); healthy PDI (hPDI); unhealthy PDI (uPDI); - DP Components: PDI: Positive: Vegetables; Potatoes; Legumes; Fruit; Fruit Juices; Nuts; Whole Grains; Refined Grains; Tea and Coffee; Sugar-Sweetened and Artificially Sweetened Beverages; Sweets and Desserts. Negative: Fish or Seafood; Meat; Egg; Miscellaneous Animal Foods; Dairy; Animal Fat; - hPDI: Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Negative: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; - uPDI: Negative: Whole grains; Fruits; Vegetables; Nuts; Legumes; Vegetable oils; Tea/coffee; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; Positive: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; - DP Method(s): Index; Comparisons: Continuous, Categorical: Tertiles of PDI, hPDI, uPDI | Follow-Up Duration: 13 y; Overall PDI vs. incident CVD, HR, 95% CI; T1: REF; T2: 1.02, 95% CI: 0.75, 1.37; T3: 1.09, 95% CI: 0.80, 1.47; P-trend: 0.60; Per SD higher score: 1.07, 95% CI: 0.94, 1.22; P-value: 0.30; Healthy PDI vs. incident CVD, HR, 95% CI; T1: REF; T2: 0.97, 95% CI: 0.72, 1.29; T3: 1.02, 95% CI: 0.76, 1.36; P-trend: 0.92; Per SD higher score: 1.04, 95% CI: 0.92, 1.18; P-value: 0.52; uPDI PDI vs. incident CVD, HR, 95% CI; T1: REF; T2: 1.01, 95% CI: 0.83, 1.45; T3: 1.03, 95% CI: 0.76, 1.40; P-trend: 0.82; Per SD higher score: 1.05, 95% CI: 0.93, 1.19; P-value: 0.42; Stratified by sex; Overall PDI vs. incident CVD, HR, 95% CI (highest vs. lowest tertile); Female, T1: REF; T3: 1.02, 95% CI: 0.99, 1.05; Male, T1: REF; T3: 0.99, 95% CI: 0.95, 1.03; P-interaction: 0.13; Healthy PDI (tertile) vs. incident CVD, HR, 95% CI (highest vs. lowest tertile); Female, T1: REF; T3: 1.01, 95% CI: 0.98, 1.04; Male, T1: REF; T3: 0.99, 95% CI: 0.95, 1.03; P-interaction: 0.47; Unhealthy PDI (tertile) vs. incident CVD, HR, 95% CI; (highest vs. lowest tertile); Female, T1: REF; T3: 1.00, 95% CI: 0.97, 1.03; Male, T1: REF; T3: 1.00, 95% CI: 0.96, 1.04; P-interaction: 0.80; Overall PDI vs. incident CHD, HR, 95% CI; T1: REF; T2: 1.02, 95% CI: 0.69, 1.51; T3: 1.13, 95% CI: 0.76, 1.69; P-trend: 0.54; Per-SD higher score: 1.10, 95% CI: 0.93, 1.31; P-value: 0.25; Healthy PDI vs. incident CHD, HR, 95% CI; T1: REF; T2: 0.92, 95% CI: 0.63, 1.35; T3: 1.04, 95% CI: 0.72, 1.53; P-trend: 0.82; Per-SD higher score: 1.07, 95% CI: 0.92, 1.27; P-value: 0.34; Unhealthy PDI vs. incident CHD, HR, 95% CI; T1: REF; T2: 1.26, 95% CI: 0.88, 1.79; T3: 0.86, 95% CI: 0.56, 1.31; P-trend: 0.53; Per-SD higher score: 1.00, 95% CI: 0.85, 1.18; P-value: 0.97; Overall PDI vs. incident stroke, HR, 95% CI; T1: REF; T2: 0.98, 95% CI: 0.65, 1.49; T3: 0.98, 95% CI: 0.64, 1.50; P-trend: 0.93; Per-SD higher score: 1.00, 95% CI: 0.84, 1.20; P-value: 0.97; Healthy PDI vs. incident stroke, HR, 95% CI; T1: REF; T2: 0.83, 95% CI: 0.55, 1.26; T3: 0.86, 95% CI: 0.46, 1.29; P-trend: 0.45; Per-SD higher score: 0.94, 95% CI: 0.79, 1.12; P-value: 0.49; Unhealthy PDI vs. incident stroke, HR, 95% CI; T1: REF; T2: 1.07, 95% CI: 0.71, 1.62; T3: 1.36, 95% CI: 0.90, 2.06; P-trend: 0.14; Per-SD higher score: 1.18, 95% CI: 0.99, 1.41; P-value: 0.07; Overall PDI vs. incident ischemic stroke, HR, 95% CI; T1: REF; T2: 0.94, 95% CI: 0.61, 1.46; T3: 0.97, 95% CI: 0.62, 1.51; P-trend: 0.88; Per-SD higher score: 0.99, 95% CI: 0.76, 1.09 P-value: 0.90; Healthy PDI vs. incident ischemic stroke, HR, 95% CI; T1: REF; T2: 0.88, 95% CI: 0.58, 1.35; T3: 0.79, 95% CI: 0.51, 1.22; P-value: 0.29; Per-SD higher score: 0.91, 95% CI: 0.76, 1.09; P-value: 0.32; Unhealthy PDI vs. incident ischemic stroke, 95% CI; T1: REF; T2: 1.05, 95% CI: 0.69, 1.62; T3: 1.26, 95% CI: 0.81, 1.94; P-value: 0.30; Overall PDI (continuous) vs. incident hemorrhagic stroke, HR, 95% CI; Per-SD higher score: 1.18, 95% CI: 0.63, 2.20; P-value: 0.60; Healthy PDI (continuous) vs. incident hemorrhagic stroke, HR, 95% CI; Per-SD higher score: 1.46, 95% CI: 0.81, 2.64; P-value: 0.21; Unhealthy PDI (continuous) vs. incident hemorrhagic stroke, HR, 95% CI; Per-SD higher score: 1.52, 95% CI: 0.82, 2.82; P-value: 0.18; Summary: NS/Null: Overall PDI, hPDI, uPDI & incident CVD; No association after stratifying by sex; NS/Null: Overall PDI, healthy PDI, unhealthy PDI and CHD, stroke (ischemic stroke and hemorrhagic stroke) | - Did not account for: None (all); - Dietary assessment: Single time point measurement of exposure; - Outcome measurement: Self-report +adjudication; - Single time point measure of exposure; - Funding: Jackson State Univeristy, Tougaloo College, Mississippi State Department of Health
Whalen, 2017^109^; United States; REGARDS; Analytic N=21,423; Participant characteristics:; - [underlined: Race and/or Ethnicity]: 81% White; 19% Black; - [underlined: SEP]: Income <$20,000/y: ~9-23%; - Health insurance: ~91-96%; - [underlined: Selection]: Excluded participants without complete FFQ at baseline and those that were lost to follow-up; - Overweight and Obesity: ~74% | - DP Age(s): ≥45 y of age at baseline; Mean age: ~64.6 y; - DP(s) examined: Mediterranean-based Diet Score (MedDietScore) [Whalen, 2014]; Paleolithic Diet Score [Whalen, 2014]; - DP Components: MedDietScore: Positive: Vegetables; Fruit; Nuts; Fish; Lean Meat (skinless chicken and turkey); MUFA/SFA ratio. Negative: Red and Processed Meat (Nitrate processed meats and red meat consumption together); Sodium. Neutral: Grains and Starches (breads, rice, and white potatoes); Dairy Foods; Alcohol; - Paleolithic Diet Score: Positive: Vegetables; Fruit and Vegetable Diversity; Fruit; Nuts; Fish; Lean Meat (skinless chicken, veal, and turkey); Calcium (from non-dairy foods). Negative: Grains and Starches (breads, rice, and white potatoes); Baked goods; Red and Processed Meat (Nitrate processed meats and non-lean red meat (including pork); Dairy Foods; Alcohol; Sodium; - DP Method(s): Index; Comparisons: Categorical: quintiles of Paleolithic, Mediterranean diet score | Follow-Up Duration: 11 y; Paleolithic Diet Score vs. CVD mortality, HR, 95% CI; Q1: REF; Q2: 1.01, 95% CI: 0.80, 1.27; Q3: 1.18, 95% CI: 0.95, 1.46; Q4: 0.94, 95% CI: 0.75, 1.18; Q5: 0.78, 95% CI: 0.61, 1.00; P-trend: 0.06; MedDietScore vs. CVD mortality, HR, 95% CI; Q1: REF; Q2: 0.92, 95% CI: 0.75, 1.13; Q3: 0.94, 95% CI: 0.76, 1.15; Q4: 0.86, 95% CI: 0.68, 1.08; Q5: 0.68, 95% CI: 0.53, 0.88; P-trend: 0.01; Summary: Inverse: Med diet and CVD mortality; Null: Paleolithic diet score and CVD mortality | - Did not account for: None (all); - Dietary assessment: Single time point measurement of exposure; - Outcome measurement: Medical records +adjudication; - Single point exposure measurement at baseline; - Funding: NIH; NINDS; HHS
Whelton, 2015^125^; United States; MESA; Analytic N=1850; Participant characteristics:; - [underlined: Race and/or Ethnicity]: 34.7% White; 11.4% Black; 29.9% Hispanic; 24.1% Asian; - [underlined: SEP]: NR; - [underlined: Selection]: Excluded participants with any CAC at MESA visit 1 and those without a repeat CAC scan at MESA visit 5; - Antihypertensive medications: 27.9%; - Lipid lowering medications: 11% | - DP Age(s): 45 to 84 y at baseline; Mean age: 57.1 y; - DP(s) examined: Mediterranean Diet Score (MDS) [Trichopolou 2003]; - DP Components: MDS (MeD): Positive: Vegetables; Legumes; Fruit; Nuts; Cereals; Fish; MUFA/SFA. Negative: Red and Processed Meat; Dairy Products. Neutral: Alcohol; - DP Method(s): Index; - Comparisons: Categorical: Binary (Above vs. below median) | Follow-Up Duration: 9.6 y; Mediterranean diet score vs. Coronary artery calcification, RR, 95% CI; No (< Median): Ref; Yes (> Median): 0.98, 95% CI: 0.88, 1.09; Summary: NS/Null: Med Diet & Coronary artery calcification | - Did not account for: None (all); - Dietary assessment: Single time point measurement of exposure; - Funding: NHLBI; NCRR
Xu, 2020^110^; United States; ARIC Study; Analytic N=10,808; Participant characteristics:; - [underlined: Race and/or Ethnicity]: 76.7 NHW; 23.3% Black; - [underlined: SEP]: 12-30%: < High school; - 70-88%: ≥high school degree; - [underlined: Selection]: Excluded participants with diabetes, CVD or cancer at baseline, implausible energy intake, missing dietary data, neither white or African American, missing covariates and missing CVD or diabetes diagnosis and prevalent diabetes, CVD or cancer prior to visit 3. | - DP Age(s): 45 to 64 y at baseline, Mean age at baseline: 53.7 y; - DP(s) examined: HEI-2015, aHEI-2010; - DP Components: HEI-2015: Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; PUFA+MUFA/SFA. Negative: Refined Grains; Added Sugars; SFA; Sodium; - aHEI-2010: Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol; - DP Method(s): Index; Comparisons: Continuous; Catergorical: Quintiles of HEI-2015, aHEI-2010 and change in HEI-2015, aHEI-2010 between visit 1 and visit 3 | Follow-Up Duration: 26 y; HEI-2015 vs CVD incidence, HR, 95% CI; Q1: REF; Q2: 0.92, 95% CI: 0.82, 1.04; Q3: 0.88, 95% CI: 0.78, 0.99; Q4: 0.86, 95% CI: 0.76, 0.97; Q5: 0.79, 95% CI: 0.70, 0.91; P-trend: <0.001; Per 10% higher diet quality score: HR: 0.90, 95% CI: 0.86, 0.95; aHEI-2010 vs. CVD incidence, HR, 95% CI; Q1: REF; Q2: 0.92, 95% CI: 0.81, 1.03; Q3: 0.89, 95% CI: 0.79, 1.01; Q4: 0.94, 95% CI: 0.84, 1.06; Q5: 0.84, 95% CI: 0.74, 0.95; P-trend: 0.03; Per 10% higher diet quality score: HR: 0.96, 95% CI: 0.93, 0.99; HEI-2015 (Categories of 6-y % changes in diet quality score) vs. CVD incidence, HR, 95% CI; No change or stable (+3%): REF; Small to moderate decrease (3-10%): 0.95, 95% CI: 0.81, 1.11; Large (>10% decrease): 1.04, 95% CI: 0.87, 1.25; Small to moderate increase (3-10%): 0.91, 95% CI: 0.78, 1.06; Large (>10% increase): 0.98, 95% CI: 0.84, 1.15; aHEI-2010 (Categories of 6-y % changes in diet quality score) vs. CVD incidence, HR, 95% CI; No change or stable (+3%): REF; Small to moderate decrease (3-10%): 1.03, 95% CI: 0.83, 1.29; Large (>10% decrease): 1.10, 95% CI: 0.91, 1.33; Small to moderate increase (3-10%): 1.13, 95% CI: 0.91, 1.40; Large (>10% increase): 1.22, 95% CI: 1.02, 1.47; HEI vs. CVD incidence by diet quality change groups; HR, 95% CI; Low-low: REF; Low-Moderate: 0.96, 95% CI: 0.79, 1.17; Low-High: 1.01, 95% CI: 0.78, 1.29; Moderate-Moderate: REF; Moderate-Low: 1.18, 95% CI: 0.93, 1.49; Moderate-High: 1.09, 95% CI: 0.89, 1.33; High-High: REF; High-Low: 1.09, 95% CI: 0.71, 1.65; High-Moderate: 1.02, 95% CI: 0.83, 1.27; aHEI-2010 vs. CVD incidence by diet quality change groups HR, 95% CI; Low-Low: REF; Low-Moderate: 0.99, 95% CI: 0.82, 1.19; Low-High: 0.94, 95% CI: 0.73, 1.21; Moderate-Moderate: REF; Moderate-Low: 1.02, 95% CI: 0.80, 1.30; Moderate-High: 1.08, 95% CI: 0.88, 1.33; High-High: REF; High-Low: 1.03, 95% CI: 0.74, 1.42; High-Moderate: 1.01, 95% CI: 0.83, 1.23; No interaction (p>0.05) between diet quality (HEI-2015, aHEI-2010) and race and/or ethnicity (African American, White) and CVD incidence; Summary: Inverse: HEI-2015, AHEI-2010 and incident CVD; Null: Change in HEI-2015 and AHEI-2010 scores and CVD incidence | - Did not account for: None (all); - Dietary assessment: Multiple exposure assessment; - Outcome measurement: Medical records; - Small sample sizes in certain buckets that might have impacted the precision. Multiple testing, p-value was not adjusted; - Funding: NHLBI/NIH
Yu, 2015^111^; United States; Southern Community Cohort Study; Analytic N=77,572; Participant characteristics:; - [underlined: Race and/or Ethnicity]: 65.01% African Americans; 31% Whites; ~4% Other race; - [underlined: SEP]: 55% income <$15,000; - ~21%-36% <12 y education; - ~50-71% with medical insurance covered; - [underlined: Selection]: Excluded participants with inadequate FFQ, implausible energy intake, missing race and/or ethnicity, and those that died 20 d after baseline survey; - Mean BMI: ~30.3 kg/m2; - Hypertension: 54.4%; - Hypercholeserolemia: 34.5%; - Former or current smoking: ~63% | - DP Age(s): 40 to 79 y at baseline; Mean age at baseline: 52.5 y; - DP(s) examined: HEI-2010; - DP Components: HEI-2010: Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; Fatty acids. Negative: Refined Grains; Added sugars in “empty calories”; Solid fats in “empty calories” ; Sodium; - DP Method(s): Index; Comparisons: Continuous; Categorical: quintiles | Follow-Up Duration: 6.2 y; HEI-2010 vs. CVD deaths, HR, 95% CI; Q1: REF; Q2: 1.05, 95% CI: 0.92, 1.19; Q3: 1.00, 95% CI: 0.88, 1.15; Q4: 0.96, 95% CI: 0.84, 1.10; Q5: 0.81, 95% CI: 0.70, 0.94; p-trend: 0.001; HEI-2010 vs. CVD deaths, HR, 95% CI in African Americans; Q1: REF; Q2: 1.09, 95% CI: 0.92, 1.28; Q3: 1.02, 95% CI: 0.87, 1.20; Q4: 0.99, 95% CI: 0.84, 1.16; Q5: 0.85, 95% CI: 0.71, 1.01; p-trend: 0.02; HEI-2010 vs. CVD deaths, HR, 95% CI in White or other race and/or ethnicity; Q1: REF; Q2: 0.98, 95% CI: 0.78, 1.23; Q3: 0.98, 95% CI: 0.78, 1.23; Q4: 0.90, 95% CI: 0.71, 1.15; Q5: 0.73, 95% CI: 0.57, 0.95; p-trend: 0.02; Summary: Inverse: HEI & CVD-mortality, overall and in African Americans and Whites or other races | - Did not account for: None (all); - Dietary assessment: Single time point measurement of exposure; - Outcome measurement: SSA + National Death Index; - Single time point measurement of exposure. Study included some participants with disease and these participants had higher HEI. However, the association persisted after adjusting for baseline disease status. Majority of the participants are African Americans with low SES, so findings may not be entirely generalizable.; - Funding: NIH
Yuan, 2023^112^; United States; NHANES; Analytic N=30,442; Participant characteristics:; - [underlined: Race and/or Ethnicity]: 66.4% NHW; 11.3% NHB 8.6% MA 5.8% Other Hispanic 7.9% Other race; - [underlined: SEP]: College or above: 61.0%; High school: 2.4%; <high school: 15.6%; - [underlined: Selection]: Excluded participants who were pregnant, without available 24-hour dietary interview data; - Mean BMI: 29.09 kg/m2; - Current or former smoker: ~45%; - Hypertension: 37.2%; - Hyperlipidemia: 68.7% | - DP Age(s): ≥20 y at baseline; Mean age: 47.7 y; - DP(s) examined: HEI-2015; - DP Components: HEI-2015: Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; PUFA+MUFA/SFA. Negative: Refined Grains; Added Sugars; SFA; Sodium; - DP Method(s): Index; Comparisons: Continuous; Catergorical HEI score (low HEI (0 ≤ HEI ≤ 44.4), medium HEI (44.4 < HEI ≤ 56.8), high HEI (56.8 < HEI ≤ 96.0) | Follow-Up Duration: 8.6 y; CVD mortality; HEI vs. Death of heart disease, HR, 95% CI; Low HEI: REF; Medium HEI: 1.16, 95% CI: 0.87, 1.53, P-value: 0.32 High HEI: 0.78, 95% CI: 0.60, 1.03, P-value: 0.08 HEI (per 1 SD increase): 0.89, 95% CI: 0.80, 0.99; P-value: 0.036; Summary: Inverse: HEI (per 1 SD) & death of heart disease; Null: HEI (categorical) & death of heart disease | - Did not account for: Race and/or ethnicity, Physical activity, Total E; - Dietary assessment: Single time point measurement of exposure; - Outcome measurement: National Death Index + ICD codes; - Single point dietary recall measurement; - Funding: CAMS Innovation Fund for Medical Sciences (CIFMS)
Zhang, 2023^113^; United States; NHANES; Analytic N=6690; Participant characteristics:; - [underlined: Race and/or Ethnicity]: 43.7% NHW; 27.8% NHB; 12.3% MA; 16.2% Other race; - [underlined: SEP]: 28.8% < High school; 25.2% High school; >46% above high school; - [underlined: Selection]: Excluded participants who reported pregnancy, cancer or no follow-up data; - 100% participants with hypertension, defined as SBP ≥40 mmHg and/or DBP ≥ 90; - BMI: 31.2 kg/m2; - CVD: 19.1%; - Hyperlipidemia: 80.1% | - DP Age(s): ≥20 y at baseline; Mean age: 55.9 y; - DP(s) examined: HEI-2010; - DP Components: HEI-2010: Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; Fatty Acids. Negative: Refined Grains; Added Sugars in “Empty Calories”; Solid Fats in “Empty Calories”; Sodium; - DP Method(s): Index; Comparisons: Categorical: Quartiles of HEI-2010 scores | Follow-Up Duration: 8.4 y; CVD mortality; HEI-2010 vs. Heart disease mortality; Q1: REF; Q2: 0.60, 95% CI: 0.44, 0.81; Q3: 0.59, 95% CI: 0.40, 0.89; Q4: 0.53, 95% CI: 0.35, 0.80; p-trend: 0.01; Per-unit increment in ln-transformed HEI-2010 scores: 0.45, 95% CI: 0.27, 0.76; P-value: 0.003; Cerebrovascular mortality; Q1: REF; Q2: 2.11, 95% CI: 0.96, 4.66; Q3: 1.26, 95% CI: 0.54, 2.93; Q4: 1.47, 95% CI: 0.62, 3.48; p-trend: 0.95; Summary: Inverse: HEI-2010 scores and heart disease mortality in hypertensive population; Null: HEI-2010 and cerebrovascular mortality | - Did not account for: None (all); - Dietary assessment: Two consecutive 24 hr recalls; - Outcome measurement: National Death Index + ICD codes; - Two consecutive 24-hr dietary recalls; - Funding: NR
Zhong VW, 2021^115^; United States; Cardiovascular Disease Lifetime Risk Pooling Project (LRPP): ARIC, CARDIA, CHS, FHS, FOS, MESA; Analytic N=29,497; Participant characteristics:; - [underlined: Race and/or Ethnicity]:; 70% White;; ~23.5% Black; ~6.4% Other; - [underlined: SEP]: Some college or more:; Young: 47-82%; Middle aged: 49-73%; Older: 42-67%; - [underlined: Selection]: Excluded participants with CVD at baseline, implausible dietary data or missing data for study variables; - Current smoker: 21.7% BMI: ~27 kg/m2 | - DP Age(s): 20 to 79 y at baseline; Mean age: 53.4 y; - DP(s) examined: Alternative HEI (AHEI)-2010 [Chiuve 2012]; - DP Components: aHEI-2010: Positive: Fruit, Vegetable, Whole grain, Nuts and legume, Energy from PUFA, EPA+DHA; Moderate: Alcohol; Negative: Sweetened beverages, Red or processed meat, Energy from trans fat, Sodium; - DP Method(s): Index; Comparisons: Categorical: Quintiles of aHEI-2010 score | Follow-Up Duration: Upto 40 y follow-up; Incident CVD (includes fatal and nonfatal CHD, stroke, heart failure and other CV deaths); Young men (20-39 y); Q1: REF; Q2: 0.95, 95% CI: 0.63, 1.43; Q3: 0.67, 95% CI: 0.40, 1.14; Q4: 0.69, 95% CI: 0.39, 1.23; Q5: 0.91, 95% CI: 0.52, 1.62; p-trend: 0.27; Middle-aged men (40-59 y); Q1: REF; Q2: 0.74, 95% CI: 0.64, 0.85; Q3: 0.77, 95% CI: 0.66, 0.90; Q4: 0.60, 95% CI: 0.50, 0.72; Q5: 0.48, 95% CI: 0.39, 0.59; p-trend: <0.0001; Older men (60-79 y); Q1: REF; Q2: 0.92, 95% CI: 0.80, 1.06; Q3: 0.86, 95% CI: 0.74, 0.99; Q4: 0.71, 95% CI: 0.61, 0.83; Q5: 0.55, 95% CI: 0.47, 0.64; p-trend: <0.0001; Young women (20-39 y); Q1: REF; Q2: 1.11, 95% CI: 0.69, 1.80; Q3: 1.05, 95% CI: 0.60, 1.82; Q4: 0.91, 95% CI: 0.49, 1.66; Q5: 0.91, 95% CI: 0.47, 1.77; p-trend: 0.66; Middle-aged women (40-59 y); Q1: REF; Q2: 0.98, 95% CI: 0.83, 1.15; Q3: 0.92, 95% CI: 0.77, 1.09; Q4: 0.74, 95% CI: 0.61, 0.89; Q5: 0.47, 95% CI: 0.37, 0.60; P-trend: <0.0001; Older women (60-79 y); Q1: REF; Q2: 1.01, 95% CI: 0.85, 1.19; Q3: 0.81, 95% CI: 0.69, 0.96; Q4: 0.71, 95% CI: 0.60, 0.84; Q5: 0.49, 95% CI: 0.41, 0.58; p-trend: <0.0001; Summary: Inverse: AHEI-2010 & CVD in middle-aged and older men and women; Null: AHEI-2010 & CVD in younger men and women | - Did not account for: Total energy intake; - Dietary assessment: Single time point measurement of exposure; - Outcome measurement: Medical records + adjudication; - Single dietary measure; - Funding: AHA, NHLBI, NorthWestern University
Zhong, 2021^114^; United States; PLCO (Prostate, Lung, Colorectal, and Ovarian Cancer Screening Trial); Analytic N=91,891; Participant characteristics:; - [underlined: Race and/or Ethnicity]: 91% NHW; 3% Blacks; 1.5% Hispanic; 4% Others; - [underlined: SEP]: 63% College below; - [underlined: Selection]: Excluded participants with a history of cancer, stroke, heart attack and participants with implausible dietary intake, invalid dietary intake, not completing questionnaire; - History of hypertension: 30.4%; - Current or former smokers: ~51%; - Overweight/Obesity: 64.9% | - DP Age(s): 55 to 74 y; Mean age: 65.3 y; - DP(s) examined: NOVA; - DP Components: UPF: Positive: soft drinks (diet/caffeinated, regular/caffeinated, diet/decaffeinated, regular/decaffeinated), cereals (Hot dogs, turkey/low fat; Hot dogs, regular; English muffins and bagels; White bread/rolls; Corn bread/muffins; Biscuits; Quick breads; Donuts, sweet rolls, Danishes, and pop tarts; Pancakes, waffles, and French toast; Ready-to-eat cereal (highly fortified); Ready-to-eat cereal (other); Cookies and brownies; Cakes (low fat); Cakes (regular); Pies, cream/custard/other; Pies, fruit; Pies, pecan; Pies, pumpkin/sweet potato; Lasagna, ravioli, shells; Macaroni and cheese; Pizza without meat); ultraprocessed fruits and vegetables (Fried potatoes; Potato salad; Fruit drinks, diet; Fruit drinks, regular), ultra-processed dairy products (Sour cream, low fat; Sour cream, regular; Cream cheese, low fat; Cream cheese, regular; Ice cream/ice milk, low fat; Regular ice cream; Frozen yogurt, ices, and sorbet; Creamed soups), meat and fish (Restaurant or industrial hamburgers; Fried chicken, dark meat/no skin; Fried chicken, dark meat/with skin; Fried chicken, white meat/no skin; Fried chicken, white meat/with skin; Fried fish, fat added; Pizza with meat), sauces and dressings (Gravy; Salad dressing, low fat on salad and vegetables; Salad dressing, nonfat on salad and vegetables; Salad dressing, regular on salad and vegetables; Mayonnaise, diet on salad; Mayonnaise, fat free on salad; Mayonnaise, regular on salad; Mayonnaise, diet on sandwich; Mayonnaise, fat free on sandwich; Mayonnaise, regular on sandwich), salty snacks (Crackers; Potato/corn/other chips; Potato/corn/other chips-low fat; Popcorn), sugary products (Candy, chocolate; Candy, not chocolate; Saccharine in coffee and tea), and margarine (Margarine, diet; Margarine, fat free; Margarine, regular; Margarine, diet on bread); - DP Method(s): Index; Comparisons: Categorical: Quintiles of energy-adjusted UPF | Follow-Up Duration: 13.5 y; CVD mortality; UPF vs. CVD mortality, HR, 95% CI; Q1: REF; Q2: 1.00, 95% CI: 0.91, 1.09; Q3: 1.01, 95% CI: 0.92, 1.11; Q4: 1.20, 95% CI: 1.09, 1.31; Q5: 1.50, 95% CI: 1.36, 1.64; p-trend: <0.001; UPF vs. heart disease mortality, HR, 95% CI; Q1: REF; Q2: 1.01, 95% CI: 0.90, 1.12; Q3: 0.99, 95% CI: 0.89, 1.11; Q4: 1.26, 95% CI: 1.13, 1.41; Q5: 1.68, 95% CI: 1.50, 1.87; P-trend: <0.001; UPF vs. Cerebrovascular disease mortality, HR, 95% CI; Q1: REF; Q2: 0.91, 95% CI: 0.76, 1.10; Q3: 1.04, 95% CI: 0.86, 1.25; Q4: 1.00, 95% CI: 0.82, 1.21; Q5: 0.94, 95% CI: 0.76, 1.17; P-trend: 0.741; Summary: Positive/Direct: UPF consumption and CVD mortality (CVD, heart disease, cerebrovascular disease) | - Did not account for: None (all); - Dietary assessment: Single time point measurement of exposure; - Outcome measurement: National Death Index + ICD codes; - Potential for misclassification of exposure; Single point measure of exposure; - Funding: None

a Abbreviations:

DM, Diabetes mellitus (T1D a/o T2D); F/U, Follow-up; HDL-C,High-density Lipoprotein Cholesterol; HS, high school; HTN, hypertension; Hx, History; ITT, intent-to-treat;LDL-C,Low-density Lipoprotein Cholesterol; N/A, Not applicable; NR, not reported; NS, not statistically significant Ob, Obesity; OW, Overweight; PA, Physical activity; PP, per-protocol SEP/SES, Socioeconomic position/status; T2D, Type 2 Diabetes; TC, total cholesterol; TG, triglyceride; Tx, Treatment; UPF, Ultra-processed food

Alcoholic beverages were included as a component (scored positively and positive or neutral within limits) of dietary patterns that showed associations with lower risk of CVD (~54 of 110 articles). However, few of these studies examined whether the association between the dietary pattern and CVD outcomes remained unchanged with removal of alcohol as a dietary pattern component;^38,104^ In addition, there was variation across dietary patterns in terms of the precise limits or threshold amounts for consumption relative to scoring procedures and specificity of types of alcoholic beverages (e.g., red wine vs. any type). In contrast, few articles (9 of 110) scored intake of alcoholic beverages negatively as a part of the overall dietary pattern and results among those studies generally showed no statistically significant associations between the dietary pattern and CVD outcomes.

Most of the reported results showed that greater alignment to a dietary pattern were significantly associated with lower risk of CVD. When stratified by CVD outcomes,

- 31 (of 46) PCS articles that assessed CVD mortality showed statistically significant associations.^22,23,38,42,44,45,51,52,58,65,67,70,73,77,78,80,83,84,89,91,94,95,97,99,102,106,109,111–113^ None of the RCT assessed CVD mortality.
- 34 (one trial, 30 PCS) of 48 articles that assessed CVD morbidity showed statistically significant findings.^20,21,24,30,31,33–36,40,43,44,47–50,52,54,58,62–64,71,73,74,82,86,90,96,101,104,110,115,123^Although 2 articles were included from the same trial, only one that assessed CVD endpoint outcomes in normotensive women showed a significant effect.
- 16 (6 RCT, 10 PCS) of 24 articles that assessed CVD intermediate outcomes showed statistically significant findings.^21,34,36,56,61,85,98,116–118,120,123,124,126,127,129^

Studies used different labels across the body of evidence, which can be broadly grouped into: Investigator-assigned diet interventions; a priori dietary patterns including “Dietary guidelines-related” (including variations of Health Eating Index (HEI) and Alternative Healthy Eating Index, such as HEI-2010, HEI-2015, AHEI-2010), “Mediterranean”, DASH, Plant-based diet scores, or other scores; a posteriori or hybrid methods (factor/cluster analysis, latent class analysis, reduced rank regression).

##### Investigator-assigned diet interventions

Six articles from 5 trials reported that adhering to an intervention compared to control diets resulted in favorable CVD morbidity and intermediate outcomes, including blood pressure, HDL-C, LDL-C and TG.^116–118,120,123,129^ (Table 11)

- CVD intermediate outcomes:
  Two articles from the DASH feeding trial showed lower SBP, DBP and HDL-C levels in participants randomized to DASH diet (characterized by increased intake of fruits and vegetables, fat-free or low-fat dairy, whole grains, poultry, fish, nuts, seeds and legumes and lower intake of saturated and total fat, cholesterol, sweets and sugar beverages and magnesium, potassium and calcium at 75^th^ percentile of US consumption), compared to fruits and vegetable diet (fruits and vegetables, nuts, seeds and legumes, high in red meats, high in total fat, saturated fat and cholesterol, high in fiber, potassium, magnesium at 75% US consumption) and/or a control diet.^116,117^ DASH diet lowered SBP by 5.3 mm Hg and 2.8 mm Hg, when compared to the control and fruit and vegetable diet.^116^ The second DASH trial conducted in participants with pre/stage 1 hypertension, showed that there was a significant reduction in SBP of ~3.81 to 5.43 mm Hg when measured every week for over 12 weeks. DBP was measured every week and consistently showed a decline (range: 0.99 to 2.35) in participants randomized to DASH diet, but this difference was statistically significant for all weeks.
  Another trial showed a significant reduction in SBP of ~9 mm Hg in the “Dietary Guidelines” diet group (characterized by increased intake of fruits including whole fruit and juice; vegetables including dark green, red and orange, beans and peas, starchy vegetables, other vegetables; grains including whole grain and enriched refined grains; meat, fish, poultry, eggs, nuts and seeds; dairy; oils; solid fats and added sugars), but not in the comparator diet group.^118^ While HDL-C reduced in both groups, LDL-C, TG and DBP were not affected by either of the diets.
  In another trial, lower LDL-C, HDL-C and DBP were reported in the Dietary Guidelines for Americans diet group (higher in vegetables, fruit, whole grains, fiber, seafood, lean meat, legumes and nuts, and low-fat dairy and lower in sodium, saturated fat, refined grains) and “Korean” diet groups (higher intakes of grains; meat, fish, eggs, and beans; vegetables; fruits; and milk and dairy products; Kimchi, fermented bean paste) when compared to participants randomized to the comparator diet group (high in sodium, saturated fat, refined grains and low in vegetables, fruit, whole grains, fiber, lean meats, and dairy). After 4 weeks of intervention, the comparator group had a mean LDL-C of 148.3 mg/dL, when compared to the Dietary Guidelines for American diet (mean LDL-C: 142.3 mg/dL) and Korean diet (mean LDL-C: 139.7 mg/dL). HDL-C was highest in the comparator group, when compared to the other two groups. DBP was lowest in the Dietary Guidelines for Americans diet (69.7 mm Hg) and was significantly different than the comparator (71.8 mm Hg). However, SBP did not differ significantly between the groups.^120^
  Van Horn et al., who only included normotensive participants also confirmed that the intervention group had lower SBP and DBP when compared to the control group.^123^ Another trial^129^ that also enrolled normotensive participants showed that SBP was lower (111.4±1.9 mm Hg) during the BOLD+ diet condition (a DASH-like diet with additional protein as lean beef) when compared to the healthy American diet condition (115.7±1.9 mm Hg). However, there was no significant difference in DBP.
  Finally, two trials showed no effect on CVD intermediate outcomes: 1) Sidahmed et al., compared ‘healthy eating’ group with a ‘Mediterranean’ group and reported no effect on BP, HDL-C, LDL-C.^121^ 2) Tussing-Humphreys et al., who predominantly enrolled Black participants, found no significant change in SBP, DBP, LDL-C, HDL-C, TG.^122^
- CVD-mortality:
  With regard to CVD morbidity, one article showed that normotensive participants randomized to intervention (reduction in fat to 20% of total energy intake, increase vegetable and fruit and grain) had lower CHD risk when compared to the control group that received printed health materials.^123^ Conversely, another article from the same trial (which included both hypertensive (~43%) and normotensive participants) did not show an effect.^119^

##### Dietary guidelines-related indices/scores

Studies showed that greater alignment to dietary guidelines-related indices/scores were associated with a lower risk of CVD mortality in 17 articles, CVD morbidity in 17 articles and CVD intermediate outcomes in three articles. (Table 12)

- Similarities across foods and food groups in Dietary Guidelines-related indices/scores include vegetables (not potatoes/French Fries), fruits, legumes and nuts, whole grains, fish/seafood and sources of unsaturated fats scored positively, alcoholic beverage intake scored as a neutral component, and red and processed meats, sources of trans/solid and/or saturated fats, added sugars (e.g. sugar-sweetened foods and beverages including fruit juice) and sodium, each scored negatively. Several scores (e.g. HEI-2010) included total protein foods and seafood/plant proteins which were scored positively and refined grains, which were scored negatively.
- CVD mortality: Of the 20 articles, 17 articles showed that greater alignment to Dietary Guidelines-related indices/scores was associated with a lower risk of CVD mortality.^22,45,51,52,67,68,70,73,77,78,80,83,84,91,111–113^ Of the three articles that reported null findings^46,53,97^ both George et al., and Sotos-Prieto et al., showed that the association was trending towards lower risk, although it was not statistically significant. Inoue-Choi was the only article that did not show a consistent directionality, but the study enrolled 100% former smokers.^53^
  ○ Four articles that assessed CVD mortality were exclusively conducted in women, three of which reported significant association^45,70,73^ and one exclusively enrolled male participants, which also reported significant findings.^80^ In terms of health status, one article reported that 100% of the participants had hypertension^113^ and another article had 100% of the participants with normal BMI^78^ both of which reported statistically significant findings.
  ○ Four articles were conducted in mostly White participants^53,70,83,97^ of which three reported significant association. In addition, five articles stratified the findings based on race and/or ethnicity and most found a consistent association between Dietary Guidelines-related indices/scores and CVD-mortality in both Black and White participants.^22,51,52,77,111^
- CVD morbidity: Of the 19 articles, 17 showed an association between higher Dietary Guidelines-related indices/scores and lower risk of CVD morbidity.^20,31,36,49,50,52,62,63,71,73,74,82,90,96,104,110,115^ While one article showed no association between AHEI and heart failure,^39^ another article almost reached significance, with lower risk of incident CVD among those who were aligned with higher HEI-2015 score (p=0.05).^30^
  ○ Six of these articles were conducted in women^20,30,36,71,73,74^ exclusively and one article was conducted in men exclusively.^49^ Two articles stratified the association by sex, with one reporting consistent association in males and females^115^ and another study showing no association in both males and females (which was consistent with the main findings).^39^
  ○ Five articles were conducted in mostly White participants^36,49,50,71,104^ and one article included 100% Hispanic participants.^31^ When stratified further by race and/or ethnicity,^30,39,52,63,90^ a consistent association between Dietary Guidelines-related indices/scores was noted for Whites. The directionality was generally consistent for Black and Hispanic, but not all findings reached statistical significance.
  ○ Two articles stratified findings by BMI.^39,63^ While the findings were consistent for participants with normal BMI (18.5-24.9 kg/m^2^) and overweight BMI (25.0-29.9 kg/m^2^), there was a non-significant increase in the risk of CVD morbidity among those with obesity (≥30 kg/ m^2^).^63^ Del Gabbo et al., stratified BMI into two groups (<25 kg/ m^2^ and ≥30 kg/m^2^), and both reported non-significant associations.
  ○ Zhong et al., and Del Gabbo et al., stratified the findings by age. While Zhong et al., reported that middle (40-59 years) and older aged (60-79 years) participants had a lower risk of CVD morbidity in both men and women, these findings were not consistent for younger participants (20-39 years).^115^ On the other hand, Del Gabbo stratified the findings by <72 years and ≥72 years and the findings were not statistically significant in both age groups.^39^
- CVD intermediate outcomes:
  ○ Three articles reported statistically significant inverse associations between Dietary Guidelines-related indices/scores and CVD intermediate outcomes.^36,56,126^ Participants were mostly White and 100% females in two articles^36,126^ and 100% American Indian in the other article.^56^ In the latter study, there was a significant interaction by diabetes status with higher AHEI scores associated with lower LDL-C in those with diabetes, but with higher LDL-C in those without diabetes.
  ○ Two articles in 100% Hispanic participants reported no significant associations between DG-related patterns (HEI and/or AHEI) and blood lipids (TG, LDL-C, HDL-C) and blood pressure (SBP, DBP).^69,85^

##### Mediterranean style scores

Higher scores on various “Mediterranean” style indices, were associated with lower CVD mortality in 14 articles, CVD morbidity in 9 articles and CVD intermediate outcomes in 5 articles.

- Similarities across “Mediterranean” indices included: scoring vegetables (not potatoes), fruits, legumes, nuts, whole grains, fish and sources of unsaturated fats (relative to saturated fats) as positive components; alcoholic beverages as neutral component; and red and processed meat as negative component.
- CVD mortality: Of the 19 articles that assessed the association between higher “Mediterranean” style score and CVD mortality, 14 articles reported lower risk.^22,32,38,42,45,51,52,80,83,91,94,97,106,109^ Cheng et al., showed an association only when Med Diet Score was continuous, but not categorical.^32^ Of the studies that showed no association, three articles reported inverse, but non-significant association.^25,88,93^ Two others did not show a consistent trend, with one of them exclusively enrolled participants with obesity and stratified the findings by metabolically healthy and unhealthy obese status.^37,79^
  ○ Three articles were conducted exclusively in women,^25,32,45^ of which two showed an association; two articles were conducted exclusively in men and both showed an association.^38,80^ A few articles stratified the results by sex and found generally consistent association in men and women.^22,51,83,94^
  ○ Five articles reported including mostly White participants,^32,37,38,83,91^ of which four showed a statistically significant association. When stratified findings by race and/or ethnicity, the results were generally consistent in direction for White, Black and Hispanic/Latino participants, but did not always reach statistical significance.^22,51,52,94^
- CVD morbidity: Of the 11 articles that assessed the association between higher “Mediterranean” style score and CVD morbidity, nine reported lower risk.^21,30,31,52,62,90,96,101,104^ Two articles that did not show significant association reported consistent directionality between higher “Mediterranean” style score and lower risk of atherosclerotic CVD and coronary artery calcification.^27,125^
  ○ Two articles reported that they exclusively enrolled female participants and both reported a significant inverse association between Mediterranean diet and CVD morbidity.^21,30^
  ○ One article enrolled 100% Hispanic participants^31^ and another one enrolled mostly White participants.^104^ Three articles further stratified the findings by race and/or ethnicity, of which all studies reported statistically significant findings for White participants. While the directionality of findings were consistent for Black participants, it did not reach statistical significance.^30,52,90^
- CVD intermediate outcomes: Of the 7 articles that assessed the association between higher “Mediterranean” style score and CVD intermediate outcomes, 5 articles reported lower risk.^21,37,85,98,126^ Of the 2 articles that showed null association, one included 100% South Asian participants^81^ and the other included 100% Puerto Rican participants.^69^

##### ‘DASH’ style scores

Higher ‘DASH’ diet scores were significantly associated with lower CVD mortality in six articles, CVD morbidity in seven articles and CVD intermediate outcomes in two articles.

- ‘DASH’-style indices scored the following components positively: vegetables (not potatoes), fruit and fruit juice, legumes and nuts, whole grains, low-fat or non-fat dairy; and the following negatively: red and processed meat, sugar-sweetened beverages, and sodium.
- CVD mortality: Of the nine articles, 5 showed associations between a higher ‘DASH’ score and lower CVD mortality risk.^45,51,52,83,97^ whereas the other four articles reported no significant associations despite consistent directionality.
  ○ Two articles exclusively enrolled female participants, of which only George et al., showed an association.^25,45^ Patel et al., exclusively enrolled male participants but did not report statistically significant association between higher DASH score and lower risk of CVD mortality.^80^ In studies that stratified by sex, the findings were generally consistent with the overall findings for males and females.^22,51,83^
  ○ Reedy et al., enrolled participants that were mostly White and showed an inverse association between better alignment to DASH score and lower risk of CVD mortality.^83^ Three articles further stratified the findings by race and/or ethnicity.^22,51,52^ Results for the White participants were generally consistent with the overall findings and statistical significance. While findings in Black participants were consistent in direction, it did not necessarily reach statistical significance at all times.
- CVD morbidity: Of the 10 articles, 5 showed an association between higher ‘DASH’ score and lower risk of CVD morbidity.^30,40,48,62,104^ Among articles that showed null association, the directionality was consistent in some studies, but not in all.
  ○ Chen et al., exclusively enrolled female participants and showed an inverse association with peripheral arterial disease.^30^ Two other articles stratified the findings by sex, but both showed null association in overall and stratified analysis.^29,39^
  ○ Wang et al., predominantly enrolled White participants and showed an inverse association between higher DASH score and lower risk of CVD morbidity (including major CVD, CHD and stroke).^104^ Four other articles stratified the findings by race and/or ethnicity.^29,30,39,52^ Two of those reported that the findings were significant in White participants,^30,52^ but not in Black and/or Hispanic participants – although the directionality was consistent in one.^30^ The other two articles showed null association in both White and Black and the directionality was somewhat inconsistent.^29,39^
- CVD intermediate outcomes: Two articles reported that alignment to ‘DASH’ score was associated with lower risk of incident hypertension.^124,126^ Thomas et al., reported that the lower risk of hypertension was noted in both Black and White participants. However, two other articles did not report a significant association between alignment to DASH score and CVD intermediate outcomes.^69,85^ Of note, both these studies enrolled 100% Hispanic participants. One other article that primarily included White participants reported that higher DASH score was not associated with SBP and DBP, except when DASH was assessed continuously, which was associated with statistically significant higher changes in SBP.^128^

##### Plant-based diet index

Greater alignment to the plant-based diet indices (PDI) and/or healthy PDI (hPDI), characterized by higher scores, was inversely associated with CVD mortality in four articles, CVD morbidity in six articles and CVD-intermediate outcome in one article.

- PDI and hPDI included the vegetables, fruits, legumes, nuts and whole grains, vegetable oils, tea and coffee scored positively and meat, fish/seafood, eggs, dairy scored negatively. Refined grains, sugar-sweetened beverages and fruit juice were scored inconsistently across studies.
- CVD mortality: Of the five articles, four showed an inverse association between higher PDI and/or hPDI scores and lower risk of CVD mortality.^23,58,65,91^ Li et al., reported a statistically significant association between higher PDI score and lower CVD mortality, but not between hPDI and CVD mortality.
  ○ Two articles further stratified by sex, showed that the findings are generally consistent with the overall findings in direction.^23,59^
  ○ Shan et al., and Baden et al., included participants that were predominantly White and both showed a statistically significant association with lower risk of CVD mortality.^23,91^ None of the studies conducted stratified analysis by race and/or ethnicity.
- CVD morbidity: Of the 8 articles, 7 showed an inverse association between higher PDI and/or higher hPDI scores and lower CVD morbidity.^24,31,58,71,86,90,104^ While Baden et al., reported significant association between higher hPDI and lower total stroke, overall PDI was not associated with stroke.
  ○ Musicus et al. exclusively enrolled female participants and the study showed an inverse association with CVD risk.^71^ Two articles stratified the findings by sex and noted that the results were mostly consistent with the overall findings.^86,108^
  ○ Three articles included participants that were predominantly White and all of them reported statistically significant associations.^24,71,86,104^ One study enrolled 100% Hispanic participants which also reported a significant association with CVD morbidity.^31^ In contrast, a study with 100% Black participants showed no association.^108^ Shan et al., conducted a stratified analysis based on race and/or ethnicity and reported that Whites had statistically significant association; while the directionality was consistent for Black and Hispanic, the findings were not statistically significant.^90^
- CVD intermediate outcomes: Of the two articles that looked at intermediate outcomes, Kim et al., reported that overall PDI was inversely associated with hypertension.^61^ However, Bhupathiraju et al., who included 100% South Asian population showed no association between PDI and lipid profile.^26^

##### Other indices/scores

Higher scores on other indices were also associated with lower risk of CVD mortality in seven articles, CVD morbidity in 11 articles and CVD-intermediate outcomes in five articles. Common elements in these patterns included vegetables, fruits, legumes, nuts and whole grains, which were scored positively, and red and processed meat which was scored negatively.

- CVD mortality:
  ○ The dietary patterns that showed an inverse association with CVD mortality included: Moderation-quantified healthy diet, alternative moderation-quantified healthy diet;^38^ a priori diet quality score;^70^ WCRF/AICR score;^89^ MIND diet score;^95^ Dietary diabetes risk score;^102^ Food Quality Score;^43^ Pro-vegetarian diet index.^58^ Two articles reported no association between Evolutionary-Concordance diet score and CVD mortality.^32,100^ Two other articles showed no association between Diet quality index (comprehensive, plant-based, animal-based) and CVD mortality.^37,57^ In addition, Ideal Diet index^37^ and Paleolithic Diet Score also showed no association.^109^
  ○ Two articles included 100% female participants^32,70^ and one study included 100% male participants.^38^ Another article stratified by sex found consistent association with the overall findings.^89^
  ○ Seven articles were conducted in mostly White participants^32,37,38,44,70,89,102^ of which five articles showed a statistically significant association.
- CVD morbidity:
  ○ The dietary patterns that showed an inverse association with CVD morbidity included: Diet composite score,^33^ A priori diet quality score,^34,35^ Minimal diet diversity score,^43^ Portfolio Diet Score,^47^ Prime Diet quality score,^49^ Food quality score,^44^ Pro-vegetarian Diet index,^58^, and Diabetes risk reduction score.^104^ Schrauben et al.,^87^ showed null association between diet score and CVD morbidity (major coronary events, ischemic stroke, heart failure) and Wang et al., did not show an association between WCRF/AICR score and major CVD, CHD and stroke.^87^ Similarly, Del Gabbo found no association between alignment to a “biologic” pattern or American Heart Association 2020 dietary goals pattern and heart failure.^39^
  ○ Glenn et al.,^47^ included 100% female participants, while Gu^49^ enrolled 100% male participants, both showed significant associations. Two additional articles that stratified the findings by sex showed that the results were mostly consistent with the overall findings.^33,43^
  ○ Three articles included predominantly White participants.^43,44,49^ Glenn et al., conducted analyses stratified by race and/or ethnicity.^47^ For total CVD and CHD, an inverse association was noted for White participants. Black and Hispanic participants had consistent directionality, but the findings did not reach statistical significance. In contrast, Asians had increased risk, although the findings were not statistically significant. For stroke, the overall findings and stratified analysis by race and/or ethnicity was not statistically significant.
- CVD intermediate outcomes:
  ○ Five of the 7 articles showed that higher scores for these patterns (i.e., Provegetarian dietary pattern, A priori diet quality score and traditional Mexican Diet, Diet quality index, Ideal Diet Index) were associated with lower risk of CVD intermediate outcomes (hypertension, elevated TG, LDL-C, non-HDL, SBP, DBP).^34,37,61,85,127^ Not all studies showed an association with all outcomes, nor did they all reach statistical significance.
  ○ Santiago-Torres et al., showed an association between traditional Mexican diet pattern and reduced HDL-C (but not elevated TG or BP) in 100% Hispanic female participants.^85^ Mattei et al., also included 100% Hispanic participants, but showed no association.^69^ Weng et al., showed null association between Healthy Food Score and hypertension, high BP.^107^

##### Factor/Cluster analysis

- CVD mortality: Of the 3 articles, 2 showed that higher dietary pattern scores assessed using factor/cluster analysis showed an inverse association with CVD mortality.^68,99^
  ○ ‘Nuts and seeds’ dietary pattern, characterized by higher intake of peanuts, tree nuts and seeds, seafood, lower in eggs, and poultry was associated with lower CVD mortality risk. However, none of the other patterns (‘Grains’, ‘Processed Foods’, ‘Meat’, ‘Legume, Fruits & Vegetables’) were associated with CVD mortality.^99^
  ○ In a multicohort study, Constellation 1 (characterized by best diet quality, exceeding fruit goals, low dairy), Constellation 2 (characterized by second best diet quality, exceeding fruit + sodium goals), Constellation 4 (characterized by exceeding greens & beans, fruit and vegetable) and Constellation 5 (characterized by lowest rank diet, exceeding seafood & plant protein) were associated with lower CVD mortality in certain cohorts.^68^
  ○ Shikany et al., reported that none of the dietary patterns examined were associated with sudden cardiac death.^93^
- CVD morbidity:
  ○ ‘Plant-based’ dietary pattern (characterized by high intake of cruciferous vegetables and other vegetables, fruit, beans, and fish) was associated with lower risk of heart failure. However, none of the other patterns were associated with heart failure risk.^64^
  ○ In another article using the same dietary patterns described above, derived using factor/cluster analysis, the ‘sweets/fats’ dietary pattern (higher intake of desserts, bread, sweet breakfast foods, chocolate, candy, solid fats and oils, and miscellaneous sugar) was associated with a lower risk of stroke.^54^
  ○ Wang et al., noted a null association between ‘PCA-Western’, ‘PCA-Prudent’, ‘RRR-Western’, ‘PLS-Western’ and Carotid plaques.^103^
- CVD-intermediate outcomes: None of the studies assessed the association between dietary patterns derived using factor/cluster analysis and CVD intermediate outcomes.

#### Dietary patterns associated with higher risk of CVD

Dietary pattern scores that are shown to be associated with an increased risk of CVD include: Unhealthy PDI (uPDI), Empirically dietary indices for hyperinsulinemia (EDIH) and empirical dietary indices for insulin resistance (EDIR), Empirical Dietary Inflammatory Pattern (EDIP), and UPF characterized by:

- UPDI is characterized by higher intake of fruit juices, sugar-sweetened beverages, refined grains; potatoes, sweets/desserts and lower intake of whole grains, fruits, vegetables, nuts, legumes; vegetable oils, tea/coffee, animal fats, dairy, eggs, fish/seafood, meat (poultry and red meat) and miscellaneous animal-based foods.
  ○ CVD mortality: Two of the 4 articles showed that higher uPDI scores were associated with a greater risk of CVD mortality.^24,65^ Of the studies that did not show an association, the directionality was consistent in one article (including when stratified by sex),^59^ but not in the other.^58^
  ○ CVD morbidity: Three of the 5 articles showed that higher uPDI scores were associated with increased risk of CVD morbidity.^24,71,86^ All three articles were conducted in predominantly White participants. Among studies that reported null findings, the directionality was consistent in one article which included 100% Black participants,^108^ but not in the other.^58^
  ○ CVD-intermediate outcomes: Of the 2 articles that assessed CVD-intermediate outcomes, 1 reported an increased risk of hypertension with increased uPDI score,^61^ whereas another article reported null findings with lipid profile.^26^
- EDIH is characterized by higher intake of processed meat, potatoes, low energy carbonated drinks and eggs and lower intake of beer, wine, coffee, snacks, fruit juice, nuts, sweets desserts, oil and vinegar salad dressing, and mayonnaise and other creamy salad dressings. EDIR is characterized by higher intake of processed meat, red meat, potatoes, low energy carbonated drinks, margarine and eggs and lower intake of dark yellow vegetables, leafy green vegetables, beer, wine, liquor, coffee, oil and vinegar salad dressing, pizza, sweets desserts, snacks, condiments and fruit juice. Both EDIR and EDIH scores were associated with higher risk of CVD mortality.^105^ Wang et al., reverse-scored EDIH and showed significantly lower risk of major CVD, CHD, stroke.^104^
- EDIP: A higher score was characterized by pro-inflammatory diet and lower score by anti-inflammatory diet. Components of pro-inflammatory diet included processed meat (sausage), red meat (beef, or lamb), organ meat (beef, calf, or chicken liver), other fish (canned tuna, or fish), other vegetables (mixed vegetables, green pepper, cooked mushroom, eggplant, zucchini, or cucumber), refined grains (white bread, biscuit, white rice, pasta, or vermicelli), high-energy and low energy beverages (cola with sugar, carbonated beverages with sugar, fruit punch drinks), and tomatoes. Components of anti-inflammatory diet included tea, coffee, dark yellow vegetables (carrots, or squash), leafy green vegetables (cabbage, spinach, or lettuce), snacks (cracker, or potato chips), fruit juice (apple juice, cantaloupe juice, orange juice, or other fruit juice), pizza. Higher EDIP scores was associated with an increased risk of total CVD, CHD and stroke^66^ and hypertriglyceridemia and low HDL-C, irrespective of their type 1 diabetes status.^76^ Wang et al., showed that reversed EDIP was associated with lower risk of major CVD, CHD, stroke.^104^
- UPF: All studies that examined dietary patterns with UPF use the Nova classification system (group 4). Two of the 3 articles reported that higher scores based on Nova group 4 were associated with a higher risk of CVD mortality^55,114^ while one article showed no association.^60^ Both articles that assessed CVD morbidity reported higherrisk.^41,55^ None of the articles assessed CVD-intermediate outcomes.
- Other patterns:
  ○ A dietary pattern derived using reduced rank regression characterized by positive components such as Fats and oils; Poultry; Non-diet soda; Processed meat; Tomatoes; Legumes; Chicken, tuna, and egg salad; Fried potatoes and negative components such as Dark-yellow vegetables; Cruciferous vegetables was associated with increased risk of stroke.^72^
  ○ Higher ‘healthy’ dietary pattern score characterized by positive components such as Cruciferous vegetables, fruits (excluding fruit juice), carotene vegetables, other vegetables, fish & seafood, poultry, dark-leaf vegetables, whole grains, tomatoes, legumes, low-fat dairy, yogurt, fruit juice, potatoes, nuts & peanut butter, fat, diet soda, tea, high-fat dairy, red meat, dessert, ice cream and negative components such as Sweets, eggs, coffee, processed meat, refined grains, fried food, sugar-sweetened beverage was associated with an increased risk of peripheral arterial disease.^75^ On the other hand, a ‘Western’ dietary pattern (characterized by positive components including processed meats, fried food, refined grains, red meat, eggs, dessert, high-fat dairy, sugar-sweetened beverages, fat, sweets, legumes, potatoes, ice cream, other vegetables, nuts & peanut butter, coffee, tomatoes, tea, dark-leaf vegetables, carotene vegetables and negative components including diet soda, fish & seafood, poultry, cruciferous vegetables, fruits (excluding fruit juice), whole grains, low-fat dairy, yogurt; Neutral: Fruit juice) was trending towards increased risk of peripheral arterial disease, but the findings were not statistically significant.^75^
  ○ Higher ‘Southern’ dietary pattern score (derived using factor/cluster) characterized by positive components such as 100% fruit juice; Added fats; Bread; Egg and egg dishes; Fried food; Fried potatoes; Milk – High-fat; Miscellaneous sugar; Organ meat; Processed meats; Red meat; Refined grains; Shell fish; Soda; SSB Negative: Cereal-high fiber; Coffee; Low-fat dairy; Milk – Low-fat; Vegetable - green leafy; Yogurt was associated with greater risk of CHD. Other patterns such as ‘Convenience’, ‘plant-based’, ‘sweets/fats’ and ‘alcohol and salads’, were not associated with CHD.^92^

### Conclusion statement and grade

The 2025 Dietary Guidelines Advisory Committee updated the existing systematic review^*^ to answer the question “What is the relationship between dietary patterns consumed and risk of cardiovascular disease for children and adolescents?” by synthesizing an additional 110 articles that met inclusion criteria, which were published between January 2014 and May 2023 (see Table 9).

* Boushey C, Ard J, Bazzano L, Heymsfield S, Mayer-Davis E, Sabaté J, Snetselaar L, Van Horn L, Schneeman B, English LK, Bates M, Callahan E, Butera G, Terry N, Obbagy J. Dietary Patterns and Risk of Cardiovascular Disease: A Systematic Review. July 2020. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at:

Table 9 Conclusion statement and grade for dietary patterns consumed by adults and older adults and risk of cardiovascular disease

Conclusion Statement | Dietary patterns consumed by adults and older adults that are characterized by higher intakes of vegetables, fruits, legumes, nuts, whole grains, unsaturated relative to saturated fats and lower sodium, and lower intakes of red and processed meat, refined grains, and sugar-sweetened foods and beverages are associated with lower risk of cardiovascular disease, including clinically meaningful improvements in blood lipids and blood pressure. Some of these dietary patterns also included low-fat dairy and seafood. These findings were consistent across diverse racial/ethnic groups and socioeconomic positions. This conclusion statement is based on evidence graded as strong. (Grade: Strong)
Grade | Strong
Body of Evidence | 110 articles (9 from trials (7 RCTs); 101 from observational studies) assessed as they related to the evidence in the existing review (101 articles)
Consistency | Some concerns with consistency, with a few studies reporting non-significant findings, although, the directionality of findings was generally consistent for many studies.
Precision | Interventions demonstrated adequate power/sample sizes. Observational studies had large sample sizes and reported results with narrow confidence intervals.
Risk of bias | Some concerns for intervention studies due to selection of reported results, and deviations from intended interventions. Some concerns due to missingness and important confounding domains (key confounders that were generally not accounted: socioeconomic position, anthropometry and physical activity).
Directness | The populations, intervention/exposure, comparators, and outcomes were directly related to the systematic review question in most studies.
Generalizability | All studies were conducted in the U.S., and the findings were reflective of the U.S. population.

#### Assessment of Evidence

This body of evidence includes 110 articles published since 2014, assessed as they relate to the evidence included in the existing review^*^ that met inclusion criteria and examined dietary patterns consumed during adulthood and older adulthood and risk of cardiovascular diseases. This body of evidence included both large and small studies with significant as well as null findings, so publication bias may have been less likely. As outlined and described below, the body of evidence was assessed for the following elements used when grading the strength of evidence.

* Dietary Patterns Technical Expert Collaborative and NESR Staff. A Series of Systematic Reviews on the Relationship Between Dietary Patterns and Health Outcomes. March 2014. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://nesr.usda.gov/sites/default/files/2019-06/DietaryPatternsReport-FullFinal2.pdf

##### Consistency

Majority of studies reported statistically significant findings that were consistent for trials and observational studies. While some studies reported associations that were not statistically significant between dietary pattern and risk of CVD, the direction of these associations were generally consistent with those that reported statistically significant inverse or positive associations. Additionally, some studies conducted stratified analysis by race and/or ethnicity, which reported that the directionality was similar for the overall findings as well as across different racial/ethnic groups. Similarly, studies that enrolled participants across different socioeconomic positions also demonstrated consistent associations. Many studies noted that lower CVD risk was associated with the consumption of dietary patterns characterized by high or higher intakes of vegetables, fruits, legumes, nuts, whole grains, and low or lower consumption of red and processed meat, sugar-sweetened foods and beverages, richer in unsaturated fats and lower in sodium and saturated fat. A small subset of studies also found evidence that dietary patterns that were lower in vegetables, fruits, legumes, nuts, whole grains and higher in refined grains, sugar-sweetened foods and beverages was associated with greater CVD risk. The heterogeneity in findings between two articles from the Women’s Health Initiative trial could be attributable to the differences in underlying health status (i.e. one study only looked at normotensive women). Five articles compared different interventions (i.e. ‘Dietary Guidelines for Americans’ diet, ‘DASH’, ‘Korean’ diet, BOLD+) to ‘Typical American Diet’ or ‘Healthy American Diet’ and all studies showed significant effects on CVD intermediate outcomes.

##### Precision

This body of evidence included a large trial, contributing two articles with sample sizes of N=10,371 and N=48,835. Other trials had reasonable sample size and/or were powered to assess the relationship between dietary patterns and CVD. Almost all observational studies had large sample sizes (~20% of the included articles >100,000 participants) and were well-powered. The studies also demonstrated minimal variance, as demonstrated by narrow confidence interval.

##### Risk of bias

A few trials had a high risk of bias because of the deviation from intended intervention and selection of reported results. Some observational studies had higher risk of bias primarily driven by confounding and missingness domains. Although many key confounders were consistently accounted for, socioeconomic position, anthropometry and physical activity were a few that were missed by some articles. Studies also received a higher risk of bias rating for the missingness domain. This was primarily driven by missingness either in exposure, outcome or covariate data and without adequately accounting for it in the analysis or when studies did not clarify whether non-participants were similar or different compared the participants. Studies also received a higher risk of bias rating because the exposure was assessed at a single time point and did not full account for the change in dietary patterns that might have occurred during years of follow-up. Considering the observational study design, studies rarely had a pre-specified analysis plan and/or sometimes conducted multiple exposure and outcome analysis, which also resulted in a higher risk of bias for selection of reported results. (Table 13 and Table 14)

Table 13 Risk of bias for intervention studies examining dietary patterns consumed by adults and older adults and risk of CVD^a^

Article | Randomization | Deviations from the intended interventions (effect of assignment) | Deviations from intended interventions (effect of assignment) or (per-protocol) | Missing outcome data | Outcome measurement | Selection of the reported result | Overall risk of bias
Jeong, 2023^116^ | LOW | SOME CONCERNS | Not Applicable | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Juraschek, 2017^117^ | LOW | SOME CONCERNS | Not Applicable | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Krishnan, 2018^118^ | LOW | LOW | Not Applicable | SOME CONCERNS | LOW | LOW | SOME CONCERNS
Prentice, 2019^119^ | LOW | HIGH | Not Applicable | LOW | LOW | LOW | HIGH
Schroeder, 2015^120^ | LOW | SOME CONCERNS | Not Applicable | SOME CONCERNS | LOW | LOW | SOME CONCERNS
Sidahmed, 2014^121^ | LOW | SOME CONCERNS | Not Applicable | SOME CONCERNS | LOW | HIGH | HIGH
Tussing-Humphreys, 2022^122^ | LOW | LOW | HIGH | LOW | LOW | LOW | HIGH
Van Horn, 2020^123^ | LOW | LOW | Not Applicable | LOW | SOME CONCERNS | HIGH | HIGH
Roussell, 2014^129^ | SOME CONCERNS | Not Applicable | LOW | LOW | LOW | LOW | SOME CONCERNS

a Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898. doi:10.1136/bmj.l4898 31462531 .

Table 14 Risk of bias for observational studies examining dietary patterns consumed by adults and older adults and risk of CVD^a^

Author, year | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall
Agha, 2014^20^ | LOW | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Ahmad, 2018^21^ | HIGH | SOME CONCERNS | LOW | HIGH | HIGH | LOW | SOME CONCERNS | HIGH
Aigner, 2018^22^ | LOW | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Baden, 2019^23^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Baden, 2021^24^ | HIGH | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH
Bertoia, 2014 (Med Diet)^25^ | LOW | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Bertoia, 2014 (DASH)^25^ | SOME CONCERNS | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Bhupathiraju, 2022^26^ | LOW | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Booth, 2016^27^ | HIGH | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Buijsse, 2015^127^ | HIGH | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Campos, 2019^28^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Chang, 2021^29^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Chen YY, 2022^31^ | LOW | SOME CONCERNS | LOW | LOW | SOME CONCERNS | HIGH | SOME CONCERNS | HIGH
Chen G, 2021^30^ | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | HIGH
Cheng, 2018^32^ | LOW | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Chiuve, 2014^33^ | HIGH | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Choi, 2021^35^ | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS
Choi, 2022^34^ | LOW | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Chomistek, 2015^36^ | HIGH | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS | HIGH
Cuenca-Garcia, 2014^37^ | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Dai, 2016^38^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | HIGH | HIGH
Del Gabbo, 2015^39^ | LOW | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Djousse, 2018^40^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Du, 2021^41^ | LOW | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Fan, 2023^42^ | LOW | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Fung, 2016^44^ | SOME CONCERNS | LOW | LOW | LOW | HIGH | SOME CONCERNS | SOME CONCERNS | HIGH
Fung, 2018^43^ | SOME CONCERNS | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
George, 2014^45^ | LOW | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
George, 2021^46^ | LOW | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Glenn, 2021^47^ | LOW | LOW | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Goyal, 2021^48^ | LOW | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Gu, 2022^49^ | SOME CONCERNS | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Guasch-Ferré, 2022^50^ | HIGH | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Harmon, 2015^51^ | LOW | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Hu, 2019^52^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Inoue-Choi, 2022^53^ | HIGH | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | HIGH
Jiang, 2015^128^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Judd, 2013^54^ | HIGH | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Juul, 2021^55^ | LOW | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Kauffman, 2020^56^ | LOW | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Keaver, 2021^57^ | LOW | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Kim, 2018^59^ | LOW | HIGH | LOW | LOW | LOW | LOW | SOME CONCERNS | HIGH
Kim, 2019^58^ | LOW | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Kim, 2019^60^ | LOW | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Kim, 2020^61^ | LOW | SOME CONCERNS | LOW | LOW | HIGH | SOME CONCERNS | SOME CONCERNS | HIGH
Kim, 2021^62^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Kong, 2021^63^ | SOME CONCERNS | HIGH | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Lara, 2019^64^ | LOW | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Li, 2016^126^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH
Li, 2018^67^ | HIGH | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Li, 2020^66^ | LOW | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Li, 2022^65^ | LOW | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Liese, 2021^68^ | LOW | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Mattei, 2017^69^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | LOW | LOW | SOME CONCERNS
Mursu, 2013^70^ | LOW | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Musicus, 2022^71^ | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS
Nazari, 2018^72^ | HIGH | SOME CONCERNS | LOW | LOW | HIGH | SOME CONCERNS | SOME CONCERNS | HIGH
Neuhouser, 2023^73^ | LOW | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Noel, 2020^74^ | SOME CONCERNS | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Ogilvie, 2017^75^ | HIGH | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | HIGH
Pang, 2021^76^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Panizza, 2018^77^ | LOW | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Park, 2016^79^ | LOW | SOME CONCERNS | LOW | LOW | LOW | LOW | HIGH | HIGH
Park, 2016^78^ | LOW | SOME CONCERNS | LOW | LOW | LOW | LOW | HIGH | HIGH
Patel, 2021^80^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Rai, 2023^81^ | LOW | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Rebholtz, 2020^82^ | HIGH | SOME CONCERNS | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH
Reedy, 2014^83^ | LOW | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Reedy, 2018^84^ | LOW | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Santiago-Torres, 2021^85^ | LOW | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Satija, 2017^86^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS
Schrauben, 2021^87^ | HIGH | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | HIGH
Shah, 2018^88^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Shams-White, 2022^89^ | LOW | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Shan, 2020^90^ | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS
Shan, 2023^91^ | LOW | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Shikany, 2015^92^ | LOW | SOME CONCERNS | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH
Shikany, 2021^93^ | LOW | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Shvetsov, 2016^94^ | LOW | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Song, 2023^95^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Sotos-Prieto, 2015^96^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | SOME CONCERNS | SOME CONCERNS | HIGH
Sotos-Prieto, 2017^97^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Steffen, 2014^98^ | HIGH | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS | HIGH
Tharrey, 2018^99^ | LOW | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Thomas, 2018^124^ | LOW | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Troeschel, 2021^100^ | LOW | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Tsivgoulis, 2015^101^ | LOW | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Wang, 2020^103^ | LOW | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Wang, 2021^102^ | LOW | SOME CONCERNS | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH
Wang, 2022^105^ | HIGH | HIGH | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Wang, 2023^106^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Wang, 2023^104^ | LOW | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Weng, 2013^107^ | LOW | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Weston, 2022^108^ | LOW | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Whalen, 2017^109^ | LOW | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Whelton, 2015^125^ | LOW | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Xu, 2020^110^ | LOW | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Yu, 2015^111^ | LOW | SOME CONCERNS | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Yuan, 2023^112^ | HIGH | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Zhang, 2023^113^ | LOW | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Zhong, 2021^114^ | LOW | HIGH | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Zhong VW, 2021^115^ | LOW | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS

a Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the “Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)” tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.

##### Directness

Most studies included in this body of evidence were designed to assess the relationship between dietary patterns and risk of CVD.

##### Generalizability

This body of evidence only included studies that were conducted in the U.S. The health status of the participants is reflective of the U.S. population with several trials exclusively enrolling participants with overweight and/or obesity. Similarly, many observational studies also included participants with overweight, obesity, hypertension, metabolic syndrome, and risk of other CVD diseases, including stroke. Although several studies included mostly White participants, some studies exclusively or predominantly enrolled participants from other race/ethnicities including Black, American Indian, Asian including South Asian and Pacific Islander. There was a broad range of socioeconomic positions represented in the included articles, which is akin to the general U.S. population; however, this data was not presented in all articles. In terms of age range, most of the participants across studies were middle-aged adults and a few studies exclusively focused on older adults; but, it is likely that these findings are applicable to older adults, as well. The diets considered in the trials (e.g. Dietary Guidelines-related) and observational studies are reflective of diet consumed by the U.S. population. Similarly, the outcomes are relevant to the U.S. population.