# Plain language summary

### What is the question?

The question is: What is the relationship between dietary patterns consumed and risk of cardiovascular disease? The population of interest included children and adolescents, and adults and older adults.

### Why was this question asked?

This systematic review was conducted by the 2025 Dietary Guidelines Advisory Committee as part of the process to develop the Dietary Guidelines for Americans, 2025-2030.

### How was this question answered?

The Committee conducted a systematic review to answer this question with support from the USDA Nutrition Evidence Systematic Review team. This review updated existing systematic reviews that were conducted by the 2020 Dietary Guidelines Advisory Committee and the Dietary Patterns Technical Expert Collaborative as part of the Dietary Patterns Systematic Reviews Project.

### What is the answer to the question?

#### Children and Adolescents

Dietary patterns consumed by children and adolescents that are characterized by higher intakes of vegetables, fruits, legumes, nuts, whole grains, fish and/or seafood, and unsaturated fats and oils and lower intakes of red and processed meats and sugar-sweetened foods and beverages are associated with lower systolic and diastolic blood pressure and triglycerides later in life. This conclusion statement is based on evidence graded as moderate.

#### Adults and Older Adults

Dietary patterns consumed by adults and older adults that are characterized by higher intakes of vegetables, fruits, legumes, nuts, whole grains, unsaturated relative to saturated fats and lower sodium, and lower intakes of red and processed meat, refined grains, and sugar-sweetened foods and beverages are associated with lower risk of cardiovascular disease, including clinically meaningful improvements in blood lipids and blood pressure. Some of these dietary patterns also included low-fat dairy and seafood. These findings were consistent across diverse racial/ethnic groups and socioeconomic positions. This conclusion statement is based on evidence graded as strong.

### How up-to-date is this systematic review?

Conclusion statements from this review are based on articles published between January 1980 and May 2023.