# Acknowledgments and funding

The Committee members were involved in: establishing all aspects of the protocol, which presented the plan for how they would examine the scientific evidence, including the inclusion and exclusion criteria; reviewing all studies that met the criteria they set; deliberating on the body of evidence for each question; and writing and grading the conclusion statements. The Health Equity Working group members (Angela Odoms-Young, PhD, MS, Heather Eicher-Miller, PhD, Jennifer Orlet Fisher, PhD, Valarie Blue Bird Jernigan, DrPH, MPH) were involved in reviewing the protocol, deliberating on the body of evidence for adults and older adults, and reviewing the conclusion statement for adults and older adults. The NESR team, with assistance from Federal Liaisons (Kara Beckman, PhD, Julia Quam, MSPH, RDN) and Project Leadership (Eve Stoody, PhD, Janet de Jesus, MS, RD), supported the Committee by facilitating, executing, and documenting the work necessary to ensure the reviews were completed in accordance with NESR methodology.

The Committee and NESR staff thank staff from National Institutes of Health (NIH), for coordinating the peer review of this systematic review, and the peer reviewers for their time and expertise.