# Appendix 6 Dietary pattern visualization

The Committee’s synthesis was facilitated by data visualization tables that presented the dietary pattern components in each of the dietary patterns examined in the body of evidence. During evidence synthesis, these tables were used in conjunction with other materials to compare and contrast the components in the dietary patterns along with the direction, magnitude, and statistical significance of reported results. Detailed information about the synthesized body of evidence, including study and population characteristics, reported results for all relevant outcomes, key confounders accounted for, study limitations, and funding sources, are summarized in the evidence tables of this report (Table 6, Table 11, and Table 12).

Each column represents the most commonly reported foods/food groups or nutrients across dietary patterns in this body of evidence. Two additional columns, “Other, A” and “Other, B”, captured a variety of other components less frequently reported across dietary patterns that did not fit into one of the preceding columns or categories, such as fast food, ready-to-eat dishes, pizza, and chocolate. Multiple symbols in each cell mean that the dietary pattern included multiple components from that column/category. Empty cells mean that the dietary pattern did not describe a component within that column/category.

## Children and adolescents

Table A 10 Visualization of dietary pattern components across dietary patterns consumed by children and adolescents from all included studies examining the relationship between dietary patterns consumed and risk of cardiovascular disease organized alphabetically by first-author last-name^*^ * ▲ Positively-scored component, reflecting higher intake within the food category as part of the pattern; ▼ Negatively-scored component, reflecting lower intake within the food category as part of the pattern; ◀ Neutral component, reflecting moderate (in contrast to higher or lower) intake within the food category as part of the pattern. Dietary approaches included methods such as a priori index/score analysis and/or investigator-assigned intervention (RCT), a posteriori latent class (LCA) or principal component analysis (PCA), and reduced rank regression (RRR). The dietary pattern labels are abbreviated in this table due to limited space, but full details about each dietary pattern are described in Table 6. ^†^ † Abbreviations: AF, added fat; AS, added sugar; B, butter; C, coffee only; Ca+, calcium; ch, cheese; D, dairy; DP, dietary pattern; EDF, energy-dense food; Fer., Fermented; FF, fried potato or French fries; Fr, included with Fruit component; FS, fish and seafood; G, grains or cereals; HF, high-fiber; LN, legumes and nuts; M, meat and or meat products; Med, Mediterranean; Na+, sodium; NP, not processed; NS, not sweetened; oo, olive oil; P, processed; pro, protein (total/foods); RP, red and processed; SB, sugar-sweetened beverage; T, tea only; TC, tea and/or coffee; UF: SF, ratio of unsaturated relative to saturated fat; UP, ultra-processed; Vit. Vitamin; V, vegetable; VL, vegetables and legumes; W: R, white-to-red meat ratio; X, not included; y, yogurt

Article; DP Approach; Dietary pattern | Vegetables | Potato | Legumes | Fruit | Fruit Juice | Nuts, Seeds | Grains: Whole | Grains | Grains: Refined | Fish | Seafood, shellfish | Meats (Red Processed) | Lean meats (Poultry) | Eggs | Dairy | Dairy: Low, non-fat | Dairy: Whole, high fat | Sugary Beverages | Sugary foods | Fat: Unsaturated, Oils | Fat: Other | Fat: Saturated | Alcohol | Salty foods, Sodium Na^+^ | Tea and Coffee | Fiber | Other A | Other B
Asoudeh, 2023; RCT; Mediterranean (Med.) v. Control diet | ◀ | | | ◀ | | | | ◀ | | | | ◀ | | | | | | ◀ | | ▲ | ▲ | | | | | ▲
Aljahadali, 2022; a priori; aMED | ▲ | X | ▲ | ▲ | | ▲ | ▲ | | | | | ▼R▼P | | | | | | | | ▲
Aljahdali, 2022; a priori; DASH | ▲ | X | ▲ | ▲ | Fr | LN | ▲ | | | | | ▼RP | | | | ▲ | | ▼ | | | | | | ▼
Asghari, 2016; a priori; DASH | ▲ | X | ▲ | ▲ | Fr | LN | ▲ | | | | | ▼RP | | | | ▲ | | ▼ | | | | | | ▼
Buckland, 2022; a priori; C-rMED | ▲ | | ▲ | ▲ | | ▲ | ▲ | ▲ | | ▲ | ▲ | ▼ | M | | ▲ | | | | | ▲
Bull, 2016; PCA; ‘Healthy’ | ▲ | | ▲ | ▲ | ▲ | | ▲ | ▲ | | ▲ | | | | ▲ | | ▲ | | | | | | ▲ | | | | | ▲
Bull, 2016; PCA; ‘Traditional’ | ▲ | ▲ | | | | | | ▲ | | | | ▲R | ▲ | | | | | | | | | | | | ▲TC | | ▲ | ▲
Bull, 2016; PCA; ‘Packed Lunch’ | | | | | | | | | ▲ | | | ▲P | M | | | | | | ▲ | | ▲ | | | ▲ | ▲TC | | ▲
Bull, 2016; PCA; ‘Processed’ | | | ▲ | | | | | ▲ | | ▲ | | ▲P | ▲fried | | | | | ▲ | ▲ | | | | | | | | ▲ | ▲
Chan She Ping-Delfos, 2015; a priori; DGI-CA | ▲ | | ▲ | ▲ | ▲ | | ▲ | ▲ | | | | ▲R | M | | | ▲ | | | | ▲
Cosier, 2023; a priori; Dietary Score | ▲ | | | ▲ | ▼ | | | | | | | ▼P | | | ▲ | | | ▼ | ▼ | | ▼ | ▼
Costa, 2023; PCA; ‘Healthier’ | ▲ | | VL | ▲ | | | | | | | ▲ | | | | | | | | | AF | ▲AF | AF | | | | | ▲
Costa, 2023; PCA; ‘Dairy Products’ | | | | | | | | | | | | | | | ▲
Costa, 2023; PCA; ‘Fast food and Sweets’ | | | | | | | | | | | | | | | | | | ▲ | ▲ | | | | | | ▲TC | | ▲
Costa, 2023; PCA; ‘Lower Intake’ | ▼ | | ▼ | ▼ | | | | | | | ▼ | | | | ▼ | | | | | AF | ▼AF | AF
Dahm, 2016; a priori; HS-AHEI | ▲ | | ▲ | ▲ | SB | LN | ▲ | | | ▲ | | ▼RP | | | | | | ▼ | | ▲ | ▼Tr | | | ▼Na+
Farhadnejad, 2018; a priori; DASH | ▲ | X | ▲ | ▲ | Fr | LN | ▲ | | | | | ▼RP | | | | ▲ | | ▼
Kerr, 2021; a priori; Dietary Score | ▲ | | | ▲ | | | | | | | | | | | ▲ | | | ▼ | ▼ | | ▼
Krijger, 2021; a priori; DASH | ▲ | X | ▲ | ▲ | Fr | LN | ▲ | | | | | ▼RP | | | | ▲ | | ▼ | | | | | | ▼
Krijger, 2021; a priori; CDQS | ▲ | | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼P | | | ▲ | | | ▼ | | ▲
Luque, 2021; PCA; ‘Core Foods’ | ▲ | ▲ | | ▲ | | | | | | ▲ | | ▲R | M | | | | | | | ▲oo
Luque, 2021; PCA; ‘Protein Sources’ | ▲ | ▲ | | | | | | | | ▲P | | ▲R | ▲ | ▲ | ▲ | | | | | | | | | ▲ | | | ▲
Luque, 2021; PCA; ‘Poor quality fats and sugars’ | | ▲ | | | ▲ | | | | | ▼ | | | | | ▲ch | | | | | ▼oo | | ▲ | | | ▲T
Siddiqui, 2022; a priori; CDQS | ▲ | | | ▲ | | ▲ | ▲ | | | ▲ | | ▼RP | M | | ▲ | | | ▼ | | ▲
Leffa, 2021; a priori; UPF-NOVA | | ▲FF | | | | | | | ▲ | | | ▲P | | | ▲ | | | ▲ | ▲ | | ▲ | | | ▲ | | | ▲
McCourt, 2014; a priori; MDS | ▲ | | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼RP | | | ▼ | | | | | ▲ | | | ◀
Montejano Vallejo, 2022; a priori; DI-EAT | ▲ | ◀ | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼RP | ▼ | ◀ | ◀ | | | ▼ | ▼ | ▲ | ◀ | ▼
Pinto, 2020; PCA; ‘PCA-1’ | | ▲FF | | ▼ | ▲ | | | | | ▼ | FS | ▲P | | | ▲ | | | ▲ | ▲ | | ▲ | ▲ | | ▲ | ▲C | | ▲ | ▼
Pinto, 2020; PCA; ‘PLS-1’ | | | | | | | | ▲ | | | | ▲P | | | ▲ch | | ▼ | ▲ | ▲ | | | | | | ▲C | | ▼
Pinto, 2020; PCA; ‘PCA-2’ | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▲ | FS | ▲P | | ▲ | ▲ch,y | ▲Milk | | | | | ▲B | | | ▲ | | | ▲ | ▲
Pinto, 2020; PCA; ‘PLS-2’ | | ▼FF | | | | | | | ▼ | ▲ | FS | ▼RP | | | | | | ▼ | ▼ | | | | | ▼ | | | ▼ | ▼
Pinto, 2020; PCA; ‘Energy-dense foods’ | | | | | | | | | | | | ▲P | | | | | | ▲ | ▲ | | | | | ▲
Pinto, 2020; PCA; ‘Snacking’ | ▼ | ▼ | | | | | | ▼ | | ▼ | | ▼M | M | ▼ | | | | | | | | | | | | | ▲
Pinto, 2020; PCA; ‘Healthier’ | ▲ | | | | | | | | | ▲ | | ▼P | | | | | | ▼ | ▼ | | | | | ▼ | | | ▲
Rauber, 2015; a priori; UPF-NOVA 4 | ▲UP | | | | | | ▲ | ▲ | | | | ▲P | | | | | | ▲ | ▲ | | | | | ▲
Rauber, 2015; a priori; UPF-NOVA 3 | ▲ | | | | | | | | | ▲ | | ▲P | | | ▲ch | | | ▲ | ▲ | ▲AF | | | | ▲

## Adults and older adults

Table A 11 Visualization of dietary pattern components across dietary patterns from intervention studies evidence in adults and older adults examining the relationship between dietary patterns consumed and risk of cardiovascular disease organized by first-author last-name alphabetically^*^ * ▲ Positively-scored component, reflecting higher intake within the food category as part of the pattern; ▼ Negatively-scored component, reflecting lower intake within the food category as part of the pattern; ◀ Neutral component, reflecting moderate (in contrast to higher or lower) intake within the food category as part of the pattern. Dietary approaches included in this table are a priori investigator-assigned diet intervention and/or index/score analysis. The dietary pattern labels are abbreviated in this table due to limited space, but full details about each dietary pattern are described in Table 11. ^†^ † Abbreviations: AF, added fat; AP, animal products; AS, added sugar; C, coffee; CG, control group; ch, cheese; D, dairy/products; DG, dietary guidelines; DP, dietary pattern; evo, extra-virgin olive oil; fer, fermented; FF, fried potato or French fries; Fr, included with Fruit component; FrV, fruits and vegetables; FS, fish and seafood; G, grains or grain products; HF, high-fiber; IG, intervention group; L, legumes; LN, legumes and nuts; M, meat/ products; Med, Mediterranean; NHW, Non-Hispanic White; Na+, sodium; NP, not processed; NS, not sweetened; oo, olive oil; P, processed; pro, protein (total/foods); RP, red and processed; rw, red wine; SB, sugar-sweetened beverage; SF, saturated fat; SO, sunflower oil; T, tea; Tr, Trans fat; UF, unsaturated; UF:SF, ratio of unsaturated relative to saturated fat; UP, ultra-processed; V, vegetable; VO, vegetable oil; w, wine; W:R, white-to-red meat ratio; X, component excluded from the dietary pattern; y, yogurt

Article; Dietary pattern approach and label; Key health equity data^*^; * Health equity (HE) was a focus of this review. Relevant data noted here includes studies with a majority of participants reporting lower SEP or race and/or ethnicity other than Non-Hispanic White (NHW) race/ethnicity, but more details are described in Table 11 of the main document. | Vegetables | Potato | Legumes | Fruit | Fruit Juice | Nuts, Seeds | Grains: Whole | Grains | Grains: Refined | Fish | Seafood, shellfish | Meats (Red, Processed) | Lean Meat (Poultry) | Eggs | Dairy | Dairy: Low, non-fat | Dairy: Whole, high fat | Sugary Beverages | Sugary foods | Fat: Unsaturated | Fat: Other | Fat: Saturated | Alcohol | Sodium or salty foods | Tea and Coffee | Other, A | Other, B
Jeong, 2023; RCT: DASH v. CG diets; HE:≤40% NHW | ▲ | | ▲ | ▲ | | L | ▲ | | | ▲ | | ▼RP | ▲ | | | ▲ | | ▼ | ▼ | | ▼ | ▼ | | | | ▲
Jeong, 2023; RCT: DASH v. F/V diets; HE:≤40% NHW | ▲ | | ◀ | ▲ | | L | ▲ | | | ▲ | | ◀R | ▲ | | | ▲ | | ▼ | ▼ | | ▼ | | | | | ▼ | ▲
Jeong, 2023; RCT: F/V v. CG diets; HE:≤40% NHW | ▲ | | ▲ | ▲ | Fr | L | | | | | | ◀R | | | | | | | ◀ | ▲tot. | UF | UF | | | | ▲
Juraschek, 2017; RCT: DASH diet; HE:≤40% NHW | ▲ | | ▲ | ▲ | | L | ▲ | | | ▲ | | ▼R | ▲ | | | ▲ | ◀ | ▼ | ▼ | | ◀ | | | ▼
Krishnan, 2018; RCT: DGA diet | ▲ | | ▲ | ▲ | | ▲ | ▲ | ▼ | ▼ | ▲ | FS | ▼ | M | M | ▲ | D | D | | ▼ | | ▼AS
Prentice, 2019; RCT: IG v. CG diet | ▲ | | | ▲ | | | | ▲ | | | | | | | | ▲ | | | | | ▼
Roussell, 2014; RCT: DASH v. HAD | ▲ | | ▲ | ▲ | Fr | L | ▲ | ▼ | ▼ | ◀ | | ◀R | F | ◀ | | ▲ | ▼ | ▼ | ▼ | ▼ | ▼ | ▼ | | ▼ | | ▲
Roussell, 2014; RCT: BOLD v. HAD | ▲ | | ▲ | ▲ | Fr | L | ▲ | ▼ | ▼ | ▼ | | ▲R | F | ▼ | | ▲ | ▼ | ▼ | ▼ | ▼ | ▼ | ▼ | | ▼ | | ▲
Roussell, 2014; RCT: BOLD+ v. HAD | ▲ | | ▲ | ▲ | Fr | L | ▲ | ▼ | ▼ | ▼ | | ▲R | F | ▲ | | ▲ | ▼ | ▼ | ▼ | ▼ | ▼ | ▼ | | ◀ | | ▲
Schroeder, 2015; RCT: DGA (2010) | ▲ | | ▲ | ▲ | | L | ▲ | | ▼ | | ▲ | | ▲ | | | ▲ | | | | | | ▼ | | ▼ | | ▲
Schroeder, 2015; RCT: Korean Diet | ▲▲fer | | ▲ | ▲ | | | ▲ | ▲ | ▲ | L | L | L | ▲ | L | ▲ | D | D | | | | | ◀ | | ◀
Schroeder, 2015; RCT: Korean Diet | ▲▲fer | | ▲ | ▲ | | | ▲ | ▲ | ▼ | L | L | L | ▲ | L | ▲ | D | D | | | | | ▼ | | ▼
Sidahmed, 2014; RCT: HE' v. Med arms | ▲ | | | ▲ | | | ▲ | | | | | | | | | | | | | ▲
Tussing-Humphreys, 2022; RCT: MedDiet Score; HE:≤40% NHW | ▲ | ▲ | ▲ | ▲ | | L | ▲ | | | ▲ | | ▼ | ▼ | | | | ▼ | | | ▲oo | | | ◀w
Van Horn, 2021; RCT: IG v. CG | ▲ | | | ▲ | | | | ▲ | | | | | | | | | | | | | ▼

Table A 12 Visualization of dietary pattern components across dietary patterns from observational studies in the U.S. that examined the relationship between dietary patterns consumed by adults and older adults and risk of cardiovascular disease organized by first-author last-name alphabetically^*^ * ▲ Positively-scored component, reflecting higher intake within the food category as part of the pattern; ▼ Negatively-scored component, reflecting lower intake within the food category as part of the pattern; ◀ Neutral component, reflecting moderate (in contrast to higher or lower) intake within the food category as part of the pattern. Dietary approaches included in this table are a priori investigator-assigned diet intervention and/or index/score analysis. The dietary pattern labels are abbreviated in this table due to limited space, but full details about each dietary pattern are described in Table 12. ^†^ † Abbreviations: AF, added fat; AP, animal products; AS, added sugar; C, coffee; CG, control group; ch, cheese; D, dairy/products; DG, dietary guidelines; DP, dietary pattern; evo, extra-virgin olive oil; fer, fermented; FF, fried potato or French fries; Fr, included with Fruit component; FrV, fruits and vegetables; FS, fish and seafood; G, grains or grain products; HF, high-fiber; IG, intervention group; L, legumes; LN, legumes and nuts; M, meat/ products; Med, Mediterranean; NHW, Non-Hispanic White; Na+, sodium; NP, not processed; NS, not sweetened; oo, olive oil; P, processed; pro, protein (total/foods); RP, red and processed; rw, red wine; SB, sugar-sweetened beverage; SF, saturated fat; SO, sunflower oil; T, tea; Tr, Trans fat; UF, unsaturated; UF:SF, ratio of unsaturated relative to saturated fat; UP, ultra-processed; V, vegetable; VO, vegetable oil; w, wine; W:R, white-to-red meat ratio; X, component excluded from the dietary pattern; y, yogurt

Article; Dietary pattern approach and label; Key health equity data^‡^; ‡ Health equity (HE) was a focus of this review. Relevant data noted here includes studies with a majority of participants reporting lower SEP or race and/or ethnicity other than Non-Hispanic White (NHW) race/ethnicity, but more details are described in Table 12 of the main document. | Vegetables | Potato | Legumes | Fruit | Fruit Juice | Nuts, Seeds | Grains: Whole | Grains | Grains: Refined | Fish | Seafood, shellfish | Meats (Red, Processed) | Lean Meat (Poultry) | Eggs | Dairy | Dairy: Low, non-fat | Dairy: Whole, high fat | Sugary Beverages | Sugary foods | Fat: Unsaturated | Fat: Other | Fat: Saturated | Alcohol | Sodium or salty foods | Tea and Coffee | Other, A | Other, B
Agha, 2014; a priori: AHEI-2010 | ▲ | X | ▲ | ▲ | SB | L | ▲ | | | | | ▼RP | | | | | | ▼ | | ▲▲ | ▼Tr | | ◀ | ▼
Ahmad, 2018; a priori: tMED | ▲ | X | ▲ | ▲ | | Fr | ▲ | | | ▲ | | ▼ | M | | ▼ | D | D | | | ▲UF:SF | | UF:SF | ◀
Aigner, 2018; a priori: AHEI-2010; HE:≤40% NHW | ▲ | X | ▲ | ▲ | SB | L | ▲ | | | | | ▼RP | | | | | | ▼ | | ▲▲ | ▼Tr | | ◀ | ▼
Aigner, 2018; a priori: aMED; HE:≤40% NHW | ▲ | X | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼RP | | | | | | | | ▲ | | ▼ | ◀ | ▼
Aigner, 2018; a priori: DASH; HE:≤40% NHW | ▲ | X | ▲ | ▲ | Fr | L | ▲ | | | | | ▼RP | | | | ▲ | | ▼ | | | | | | ▼
Aigner, 2018; a priori: HEI-2010; HE:≤40% NHW | ▲▲L | V | V, F, M | ▲▲ | | | ▲ | | ▼ | ▲pro | pro | F (pro) | F (pro) | | ▲ | | | AS | ▼ | ▲UF:SF | ▼ | UF:SF | | ▼
Baden, 2019; a priori: hPDI | ▲ | ▼ | ▲ | ▲ | ▼ | ▲ | ▲ | | ▼ | ▼ | FS | ▼ | M | ▼ | ▼ | D | D | ▼ | ▲ | ▲VO | | ▼ | | | ▲ | ▼AP
Baden, 2019; a priori: PDI | ▲ | ▲ | ▲ | ▲ | ▲ | ▲ | ▲ | | ▲ | ▼ | FS | ▼ | M | ▼ | ▼ | D | D | ▲ | ▲ | ▲VO | | ▼ | | | ▲ | ▼AP
Baden, 2019; a priori: uPDI | ▼ | ▲ | ▼ | ▼ | ▲SB | ▼ | ▼ | | ▲ | ▼ | FS | ▼ | M | ▼ | ▼ | D | D | ▲ | ▲ | ▼VO | | ▼ | | | ▼ | ▼AP
Baden, 2021; a priori: hPDI | ▲ | ▼ | ▲ | ▲ | ▼ | ▲ | ▲ | | ▼ | ▼ | FS | ▼ | M | ▼ | ▼ | D | D | ▼ | ▲ | ▲VO | | ▼ | | | ▲ | ▼AP
Baden, 2021; a priori: PDI | ▲ | ▲ | ▲ | ▲ | ▲ | ▲ | ▲ | | ▲ | ▼ | FS | ▼ | M | ▼ | ▼ | D | D | ▲ | ▲ | ▲VO | | ▼ | | | ▲ | ▼AP
Baden, 2021; a priori: uPDI | ▼ | ▲ | ▼ | ▼ | ▲SB | ▼ | ▼ | | ▲ | ▼ | FS | ▼ | M | ▼ | ▼ | D | D | ▲ | ▲ | ▼VO | | ▼ | | | ▼ | ▼AP
Bertoia, 2014; a priori: aMDS | ▲ | | ▲ | ▲ | | L | ▲ | | | ▲ | | ▼RP | ▼ | | | | ▼ | | | ▲ | | | ◀
Bertoia, 2014; a priori: DASH | ▲ | X | ▲ | ▲ | | L | ▲ | | | | | ▼RP | | | | ▲ | | ▼ | | | | | | ▼
Bhupathiraju, 2022; a priori: ahPDI; HE:≤40% NHW | ▲▲ | ▼ | ▲ | ▲ | ▲ | ▲ | ▲ | | ▼ | ▼ | FS | ▼ | M | ▼ | ▼ | D | D | ▼ | ▲ | ▲ | | ▼ | | | ▲ | ▼AP▼▼▼
Bhupathiraju, 2022; a priori: aPDI; HE:≤40% NHW | ▲▲▲ | ▲ | ▲ | ▲ | ▲ | ▲ | ▲ | | ▲ | ▼ | FS | ▼ | M | ▼ | ▼ | D | D | ▲ | ▲ | ▲ | | ▼ | | | ▲ | ▼AP
Bhupathiraju, 2022; a priori: auPDI; HE:≤40% NHW | ▼ | ▲ | ▼ | ▼ | ▲SB | ▼ | ▼ | | ▲ | ▼ | FS | ▼ | M | ▼ | ▼ | D | D | ▲ | ▲ | ▼ | | ▼ | | | ▼ | ▲AP▲▲▲
Booth, 2016; a priori: MDS | ▲ | | ▲ | ▲ | | ▲ | | ▲ | | ▲ | | ▼RP | | | ▼ | D | D | | | ▲UF:SF | | | ◀
Campos, 2019; a priori: DASH | ▲ | X | ▲ | ▲ | Fr | L | ▲ | | | | | ▼RP | | | | ▲ | | ▼ | | | | | | ▼
Chang, 2022; a priori: mDASH; HE:Lower SEP | ▲ | X | ▲ | ▲ | Fr | | ▲ | | | ▼ | | F | F | | ▼ | D | D | | ▼ | | ▼ | ▼ | | ▼
Chen, 2021; a priori: AHEI-2010 | ▲ | X | ▲ | ▲ | | L | ▲ | | | | | ▼RP | | | | | | ▼ | | ▲▲ | ▼Tr | | ◀ | ▼
Chen, 2021; a priori: aMED | ▲ | X | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼RP | | | | | | | | ▲UF:SF | | UF:SF | ◀
Chen, 2021; a priori: DASH | ▲ | X | ▲ | ▲ | Fr | L | ▲ | | | | | ▼RP | | | | ▲ | | ▼ | | | | | | ▼
Chen, 2021; a priori: HEI-2015 | ▲▲L | V | V, F, M | ▲▲ | | | ▲ | | ▼ | ▲pro | F (pro) | F (pro) | F (pro) | | ▲ | D | D | AS | ▼ | ▲UF:SF | | ▼ | | ▼
Chen, 2022; a priori: aMED; HE:≤40% NHW; Lower SEP | ▲ | X | ▲ | ▲ | X | ▲ | ▲ | | | ▲ | FS | ▼RP | | | | | | | | ▲UF:SF | | UF:SF | ◀
Chen, 2022; a priori: HEI-2015; HE:≤40% NHW; Lower SEP | ▲▲L | V | V, F, M | ▲▲ | | | ▲ | | ▼ | ▲pro | F (pro) | F (pro) | F (pro) | | ▲ | | | AS | ▼ | ▲UF:SF | | ▼ | | ▼
Chen, 2022; a priori: hPDI; HE:≤40% NHW; Lower SEP | ▲ | ▼ | ▲ | ▲ | ▼ | ▲ | ▲ | | ▼ | ▼ | FS | ▼ | M | ▼ | ▼ | | | ▼ | ▲ | ▲ | | ▼ | | | ▲ | ▼AP
Cheng, 2018; a priori: Evolutionary | ▲ | | | ▲ | | ▲ | | ▼ | | ▲ | | ▼RP | ▲ | | ▼ | | | ▼ | ▼ | | | | ▼ | ▼ | | ▲
Cheng, 2018; a priori: mMDS | ▲ | X | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼RP | | | | | | | | ▲UF:SF | | UF:SF | ▼
Chiuve, 2014; a priori: DCS | ▲ | | | ▲ | | ▲ | | ▲ | | | | ▲RP | | | | | | ▲ | | | | | | | | ▲
Choi, 2021; a priori: APDQS | ▲▲▲▲ | ◀ | ▲▲soy | ▲▲ | ◀ | ▲ | ▲ | | ◀ | ▲▲not fried | ◀ | ▼▼P | ▲ | ◀ | | ▲ | ▼ | ▼ | ▼▼ | ▲VO | ◀ | ▼ | ▲ | ▼snack foods | ▲ | ◀◀◀◀◀ | ▼▼▼
Choi, 2022; a priori: APDQS | ▲▲▲▲ | ◀ | ▲▲soy | ▲▲ | ◀ | ▲ | ▲ | | ◀ | ▲▲not fried | ◀ | ▼▼P▼ | ▲ | ◀ | | ▲ | ▼ | ▼ | ▼▼ | ▲VO | ◀ | ▼ | ▲ | ▼snack foods | ▲ | ◀◀◀◀◀ | ▼▼▼▼▼
Chomistek, 2015; a priori: AHEI-2010 | ▲ | X | ▲ | ▲ | | L | ▲ | | | | | ▼RP | | | | | | ▼ | | ▲▲ | ▼Tr | | ◀ | ▼
Cuenca-Garcia, 2014; a priori: DQI | ▲ | | G | V | | | | ▲ | | | | | | | | | | | | ▼ | ▼ | ▼ | | ▼ | | ▼ | ▲
Cuenca-Garcia, 2014; a priori: IDI | ▲ | | ▲ | V | | L | ▲ | | | ▲ | | ▼P | | | | | | AS | ▼ | | | ▼ | | ▼
Cuenca-Garcia, 2014; a priori: MDS | ▲ | | ▲ | ▲ | | ▲ | | ▲ | | ▲ | | ▼RP | | | ▼ | | | | | ▲UF:SF | | | ◀
Dai, 2016; a priori: aMQHD | ▲ | ▲ | | ▲ | | ▲ | | ▲ | | ▲ | FS | ▲ | ▲ | ▲ | ▲ | | | | | ▲UF:SF | | | ▲ | | | ▲▲
Dai, 2016; a priori: MDS | ▲ | | ▲ | ▲ | | ▲ | | ▲ | | ▲ | | ▼RP | | | ▼ | | | | | ▲UF:SF | | | ◀
Dai, 2016; a priori: MQHD | ▲ | ▲ | | ▲ | | | | ▲ | | ▲ | FS | ▲ | ▲ | ▲ | ▲ | | | | | ▲UF:SF | | UF:SF | ▲ | | | ▲▲
Del Gobbo, 2015; a priori: AHA-2020 | ▲ | X | ▲ | V | | L | ▲ | | | ▲ | | ▼P | | | | | | ▼ | | | | ▼ | | ▼
Del Gobbo, 2015; a priori: Biologic | ▲ | | | ▲ | | ▲ | ▲ | | | ▲ | FS | ▼RP | | | | | | ▼ | | ▲UF:SF | ▼Tr | | | ▼
Del Gobbo, 2015; a priori: DASH | ▲ | X | ▲ | ▲ | Fr | L | ▲ | | | | | ▼RP | | | | ▲ | | ▼ | | | | | | ▼
Del Gobbo, 2015; a priori: mAHEI | ▲ | X | ▲ | ▲ | | L | ▲ | | | | | W/R | ▲W:R | | | | | ▼ | | ▲UF:SF | ▼Tr | | ◀ | | | ▲
Djousse, 2018; a priori: mDASH | ▲ | X | ▲ | ▲ | Fr | L | ▲ | | | | | ▼RP | | | | ▲ | | ▼
Du, 2021; a priori: UPF, Nova4 | | | | | | | | ▲ | ▲ | | | ▲ | M | | ▲4% | D4% | D4% | ▲ | ▲ | | | | ▲
Fan, 2023; a priori: aMED | ▲ | X | ▲ | ▲ | | ▲ | ▲ | | | ▲ | FS | ▼RP | | | | | | | | ▲UF:SF | | UF:SF | ◀
Fung, 2016; a priori: FQS | ▲ | ▼▼ | ▲ | ▲ | | L | ▲ | | ▼ | | | ▼R▼P | | | ▲y | | | ▼ | ▼ | | | | | | ▲C | ▼
Fung, 2018; a priori: FGI | ▲ | G | ▲ | V | | L | | ▲ | | ▲ | | F | F | ▲ | ▲ | D | D | | | ▲tot. | UF | UF
Fung, 2018; a priori: MDDW | ▲▲▲ | G | ▲ | ▲V▲ | | L | | ▲ | | | | ▲ | M | ▲ | ▲ | D | D
Fung, 2018; a priori: PDQS | ▲▲▲▲ | ▼ | ▲ | ▲▲ | SB | L | | ▲ | ▼ | ▲ | FS | ▼R▼P | ▲ | ▲ | | | ▼ | ▼ | ▼ | ▲VO | | | | | | ▼
George, 2014; a priori: AHEI-2010 | ▲ | X | ▲ | ▲ | SB | L | ▲ | | | | | ▼RP | | | | | | ▼ | | ▲▲ | | ▼ | ◀ | ▼
George, 2014; a priori: aMED | ▲ | X | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼RP | | | | | | | | ▲UF:SF | | UF:SF | ◀
George, 2014; a priori: DASH | ▲ | X | ▲ | ▲ | Fr | L | ▲ | | | | | ▼RP | | | | ▲ | | ▼ | | | | | | ▼
George, 2014; a priori: HEI-2010 | ▲▲L | V | V, F, M | ▲▲ | | | ▲ | | ▼ | ▲▲pro | FS, pro | F (pro) | F (pro) | | | ▲ | | AS | ▼ | ▲UF:SF | | ▼ | | ▼
George, 2021; a priori: HEI-2015 | ▲▲L | V | V, F, M | ▲▲ | | | ▲ | | ▼ | ▲pro | F (pro) | ▲pro | M | | ▲ | D | D | AS | ▼ | ▲ | | ▼ | | ▼
Glenn, 2021; a priori: Portfolio score | ▲pro | | V | ▲ | | ▲ | | ▲ | | | | SF | SF | SF | | | SF | | | ▲ | | ▼M | | | | ▲
Goyal, 2021; a priori: DASH | ▲ | X | ▲ | ▲ | Fr | L | ▲ | ▲ | | | | ▼RP | | | | ▲ | | ▼ | ▼ | | | | | ▼
Gu, 2022; a priori: AHEI-2010 | ▲ | X | ▲ | ▲ | | L | ▲ | | | | | ▼RP | | | | | | ▼ | | ▲▲ | ▼Tr | | ◀ | ▼
Gu, 2022; a priori: PDQS | ▲▲▲▲ | ▼ | ▲ | ▲▲ | SB | L | ▲ | | ▼ | ▲ | FS | ▼R▼P | ▲ | ▲ | | | ▼ | ▼ | ▼ | ▲VO | | | | | | ▼
Guasch-Ferré, 2022; a priori: AHEI | ▲ | X | ▲ | ▲ | | L | ▲ | | | | | W/R | ▲W:R | | | | | ▼ | | ▲UF:SF | | UF:SF | ◀ | | | ▲
Harmon, 2015; a priori: AHEI-2010; HE:≤40% NHW | ▲ | X | ▲ | ▲ | | L | ▲ | | | | | ▼RP | | | | | | ▼ | | ▲▲ | ▼Tr | | ◀ | ▼
Harmon, 2015; a priori: aMED; HE:≤40% NHW | ▲ | X | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼RP | | | | | | | | ▲UF:SF | | UF:SF | ◀
Harmon, 2015; a priori: DASH; HE:≤40% NHW | ▲ | X | ▲ | ▲ | Fr | L | ▲ | | | | | ▼RP | | | | ▲ | | ▼ | | | | | | ▼
Harmon, 2015; a priori: HEI-2010; HE:≤40% NHW | ▲▲L | V | V, F, M | ▲▲ | | | ▲ | | ▼ | ▲pro | F (pro) | F (pro) | F (pro) | | ▲ | D | D | AS | ▼ | ▲ | | ▼ | | ▼
Hu, 2019; a priori: AHEI-2010 | ▲ | X | ▲ | ▲ | SB | L | ▲ | | | | | ▼RP | | | | | | ▼ | | ▲▲ | ▼Tr | | ◀ | ▼
Hu, 2019; a priori: aMED | ▲ | X | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼RP | | | | | | | | ▲UF:SF | | UF:SF | ◀
Hu, 2019; a priori: DASH | ▲ | X | ▲ | ▲ | Fr | L | ▲ | | | | | ▼RP | | | | ▲ | | ▼ | | | | | | ▼
Hu, 2019; a priori: HEI-2015 | ▲▲L | V | V, F, M | ▲▲ | | | ▲ | | ▼ | ▲pro | F (pro) | F (pro) | F (pro) | | ▲ | D | D | AS | ▼ | ▲UF:SF | | ▼ | | ▼
Inoue-Choi, 2022; a priori: HEI-2015 | ▲▲L | V | V, F, M | ▲▲ | | | ▲ | | ▼ | ▲pro | F (pro) | F (pro) | F (pro) | | ▲ | D | D | AS | ▼ | ▲UF:SF | | ▼ | | ▼
Judd, 2013; a post.: Alcohol/salads | ▲▲ | | | | ▼100% | ▲ | | ▼ | | ▲ | ▲ | ▲R▲P | | ▲ | | | ▲ | ▼ | ▼ | | ▲ | | ▲▲▲ | | ▲ | ▲ | ▼V▼V
Judd, 2013; a post.: Convenience | ▲ | ▲fried | ▲ | | | | | ▲ | ▲ | ▲ | FS | ▲ | ▲ | | | | ▲ | | ▲ | | | | | ▲snack foods | | ▲
Judd, 2013; a post.: Healthy | ▲▲▲ | | ▲D | ▲ | ▲100% | ▲ | ▲ | | | ▲ | | | | | ▲y | ▲ | | ▼ | | | | | ▼B | | | ▲ | ▼
Judd, 2013; a post.: Southern | ▼ | ▲ | | | ▲100% | | ▼HF | ▲ | ▲ | | ▲ | ▲P▲ | | ▲ | ▼y | ▼D;milk | ▲milk | ▲ | ▲ | ▲AF | AF | AF | | | ▼C | ▲
Judd, 2013; a post.: Sweets/Fats | | ▲▲fried | | | | | ▲ | ▲ | ▲ | | | ▲RP | | | | | ▲ | | ▲ | ▲AF | AF | ▲ | | ▲snack foods | ▲ | ▲
Juul, 2021; a priori: UPF, Nova4 | | ▲ | | | | | | ▲ | ▲ | | | ▲ | | | ▲y, AS | | | ▲ | ▲ | | | ▲ | ▲ | ▲snack foods | | ▲
Kauffman, 2020; a priori: AHEI-2010; HE:≤40% NHW; Lower SEP | ▲ | X | ▲ | ▲ | SB | L | ▲ | | | | | ▼RP | | | | | | ▼ | | ▲▲ | ▼Tr | | ◀ | ▼
Keaver, 2021; a priori: aDQI | | | | | | | | | | ▲ | FS | ▼P▼NP | ▲ | ▼ | ▲ | D, M | D, M
Keaver, 2021; a priori: cDQI | ▲ | ▼ | ▲ | ▲ | ▼ | L | ▲ | | ▼ | ▲ | FS | ▼P▼NP | ▲D | ▼ | ▲ | D | D | ▼ | ▼ | ▲VO, TC | | | | | UF
Keaver, 2021; a priori: pDQI | ▲ | ▼ | ▲ | ▲ | ▼ | L | ▲ | | ▼ | | | | | | | | | ▼ | ▼ | ▲VO, TC | | | | | UF
Kim, 2018; a priori: hPDI | ▲ | ▼ | ▲ | ▲ | ▼ | ▲ | ▲ | | ▼ | ▼ | FS | ▼ | M | ▼ | ▼ | D | D | ▼ | ▲ | | | ▼ | | | ▲ | ▼AP
Kim, 2018; a priori: PDI | ▲ | ▲ | ▲ | ▲ | ▲ | ▲ | ▲ | | ▲ | ▼ | FS | ▼ | M | ▼ | ▼ | D | D | ▲ | ▲ | | | ▼ | | | ▲ | ▼AP
Kim, 2018; a priori: uPDI | ▼ | ▲ | ▼ | ▼ | ▲SB | ▼ | ▼ | | ▲ | ▼ | FS | ▼ | M | ▼ | ▼ | D | D | ▲ | ▲ | | | ▼ | | | ▼ | ▼AP
Kim, 2019; a priori: hPDI | ▲ | ▼ | ▲ | ▲ | ▼ | ▲ | ▲ | | ▼ | ▼ | FS | ▼ | M | ▼ | ▼ | D | D | ▼ | ▲ | | | ▼ | | | ▲ | ▼AP
Kim, 2019; a priori: PDI | ▲ | ▲ | ▲ | ▲ | ▲ | ▲ | ▲ | | ▲ | ▼ | FS | ▼ | M | ▼ | ▼ | D | D | ▲ | ▲ | | | ▼ | | | ▲ | ▼AP
Kim, 2019; a priori: Proveg. | ▲ | ▲ | ▲ | ▲ | | ▲ | ▲ | | ▲ | ▼ | FS | ▼ | M | ▼ | ▼ | D | D | | | | | ▼
Kim, 2019; a priori: uPDI | ▼ | ▲ | ▼ | ▼ | ▲SB | ▼ | ▼ | | ▲ | ▼ | FS | ▼ | M | ▼ | ▼ | D | D | ▲ | ▲ | | | ▼ | | | ▼ | ▼AP
Kim, 2019 UPF; a priori: UPF, Nova4 | | | | ▲UP | ▲UP | | | ▲UP | ▲UP | | | ▲UP | ▲UP | | ▲UP | ▲UP | ▲UP | ▲UP | ▲UP | | ▲UP | | ▲ | ▲snack foods | | ▲
Kim, 2020; a priori: hPDI | ▲ | ▼ | ▲ | ▲ | ▼ | ▲ | ▲ | | ▼ | ▼ | FS | ▼ | M | ▼ | ▼ | D | D | ▼ | ▲ | | | ▼ | | | ▲ | ▼AP
Kim, 2020; a priori: PDI | ▲ | ▲ | ▲ | ▲ | ▲ | ▲ | ▲ | | ▲ | ▼ | FS | ▼ | M | ▼ | ▼ | D | D | ▲ | ▲ | | | ▼ | | | ▲ | ▼AP
Kim, 2020; a priori: PDI-Rotterdam | ▲ | ▲ | ▲ | ▲ | SB | ▲ | ▲ | | ▲ | ▼ | FS | ▼ | M | ▼ | ▼ | D | D | ▲ | ▲ | ▲VO | | ▼ | ▲ | | ▲
Kim, 2020; a priori: Proveg. | ▲ | ▲ | ▲ | ▲ | | ▲ | ▲ | | ▲ | ▼ | FS | ▼ | M | ▼ | ▼ | D | D | | | | | ▼
Kim, 2020; a priori: uPDI | ▼ | ▲ | ▼ | ▼ | ▲SB | ▼ | ▼ | | ▲ | ▼ | FS | ▼ | M | ▼ | ▼ | D | D | ▲ | ▲ | | | ▼ | | | ▼ | ▼AP
Kim, 2021; a priori: AHEI-2010 | ▲ | X | ▲ | ▲ | SB | L | ▲ | | | | | ▼RP | | | | | | ▼ | | ▲▲ | ▼Tr | | ◀ | ▼
Kim, 2021; a priori: aMED modified | ▲ | | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼RP | | | | | | | | ▲UF:SF | | UF:SF | ◀
Kim, 2021; a priori: DASH, modified | ▲ | | ▲ | ▲ | Fr | L | ▲ | | | | | ▼RP | | | | ▲ | | ▼ | | | | | | ▼
Kong, 2021; a priori: AHEI-2010 | ▲ | X | ▲ | ▲ | SB | L | ▲ | | | | | ▼RP | | | | | | ▼ | | ▲▲ | ▼Tr | | ◀ | ▼
Lara, 2019; a post.: Alcohol/Salads | ▲ | | | | | | | | | | | | | | | | | | | | | | ▲▲▲ | | | ▲
Lara, 2019; a post.: Convenience | | ▲fried | | | | | | | | | | ▲ | M | | | | | | | | | | | | | ▲
Lara, 2019; a post.: Plant-based | ▲▲ | | ▲ | ▲ | | | | | | ▲
Lara, 2019; a post.: Southern | | | | | | | | | | | | ▲P▲ | | ▲ | | | | ▲ | | ▲AF | AF | AF | | | | ▲
Lara, 2019; a post.: Sweets/Fats | | | | | | | ▲ | ▲ | ▲ | | | | | | | | | | ▲▲ | | ▲ | | | | | ▲
Li, 2018; a priori: AHEI-2010 | ▲ | X | ▲ | ▲ | SB | L | ▲ | | | | | ▼RP | ▲W:R | | | | | ▼ | | ▲UF:SF | ▼Tr | | ◀ | ▼
Li, 2020; a priori: EDIP | ▼▼ | | | | ▲ | | | | ▼ | ▼ | | ▼P▼R▼ | | | | | | ▼ | | | | | | | ▲T▲C | ▲▲▲▲ | ▼
Li, 2022; a priori: hPDI | ▲ | ▼ | ▲ | ▲ | ▼ | ▲ | ▲ | | ▼ | ▼ | FS | ▼ | M | ▼ | ▼ | D | D | ▼ | ▼ | ▲ | | ▼ | | | ▲ | ▼AP
Li, 2022; a priori: PDI | ▲ | | ▲ | ▲ | ▲ | ▲ | ▲ | | ▲ | ▼ | FS | ▼ | M | ▼ | ▼ | D | D | ▲ | ▲ | ▲ | | ▼ | | | ▲ | ▼AP
Li, 2022; a priori: uPDI | ▼ | ▲ | ▼ | ▼ | ▲ | ▼ | ▼ | | ▲ | ▼ | FS | ▼ | M | ▼ | ▼ | D | D | ▲ | ▲ | ▼ | | ▼ | | | ▼ | ▼AP
Liese, 2021; a priori: HEI-2015 | ▲▲L | V | V, F, M | ▲▲ | | | ▲ | | ▼ | ▲pro | F (pro) | F (pro) | F (pro) | | ▲ | D | D | AS | ▼ | ▲UF:SF | | ▼ | | ▼
Liese, 2021; a post.: Constellation 1 | | | | ▲ | | | | | | | | | | | ▼ | D | D
Liese, 2021; a post.: Constellation 2 | | | | ▲ | | | | | | | | | | | | | | | | | | | | ▲
Liese, 2021; a post.: Constellation 3 | ▼L | | V | ▲ | | | | | | | | | | | ▲ | D | D | | | | ▼ | | | ▼
Liese, 2021; a post.: Constellation 4 | ▲L | | V | ▲ | | | ▼ | | | | | | | | ▼ | D | D | | | | | | | ▼
Liese, 2021; a post.: Constellation 5 | | | ▲pro | | | L, pro | ▼ | | | L, pro | L, pro | | | | ▼ | D | D | | | | | | | ▼
Mattei, 2017; a priori: AHA-DS; HE:≤40% NHW; Lower SEP | ▲ | | | ▲ | Fr | | ▲ | | | ▲ | | | | | | | | AS | ▼ | AF | ▼ | ▼ | ◀ | ▼
Mattei, 2017; a priori: AHEI-2010; HE:≤40% NHW; Lower SEP | ▲ | X | ▲ | ▲ | SB | L | ▲ | | | | | ▼RP | | | | | | ▼ | | ▲▲ | | ▼ | ◀ | ▼
Mattei, 2017; a priori: DASH; HE:≤40% NHW; Lower SEP | ▲ | | ▲ | ▲ | Fr | L | ▲ | | | | | ▼RP | | | ▲ | D | D | ▼ | | | | | | ▼
Mattei, 2017; a priori: HEI-2005; HE:≤40% NHW; Lower SEP | ▲▲L | | ▲ | ▲▲ | | | ▲ | ▲ | G | | | ▲ | | | ▲ | D | D | AS | ▼ | ▲ | | AS | AS | ▼
Mattei, 2017; a priori: MDS; HE:≤40% NHW; Lower SEP | ▲ | | ▲ | ▲ | | L | | ▲ | | ▲ | | ▼RP | | | ▼ | | | | | ▲UF:SF | | UF:SF | ◀
Mursu, 2013; a priori: APDQs | ▲▲▲ | ◀ | ▲▲soy | ▲ | ◀ | ▲ | ▲ | | | ▲not fried | | ▼R▼P▼ | ▲ | ◀ | | ▲ | ▼ | ▼ | ▼▼ | ▲ | ◀ | ▼ | ▲ | ▼snack foods | ▲ | ◀◀ | ▼▼▼
Mursu, 2013; a priori: AHEI-2010 | ▲ | X | ▲ | ▲ | SB | L | ▲ | | | | | ▼RP | | | | | | ▼ | | ▲▲ | | ▼ | ◀ | ▼
Musicus, 2022; a priori: AHEI-2010 | ▲ | X | ▲ | ▲ | SB | L | ▲ | | | | | ▼RP | | | | | | ▼ | | ▲▲ | | ▼ | X | ▼
Musicus, 2022; a priori: hPDI | ▲ | ▼ | ▲ | ▲ | ▼ | ▲ | ▲ | | ▼ | ▼ | FS | ▼ | M | ▼ | ▼ | | | ▼ | ▲ | ▲ | | ▼ | | | ▲ | ▼AP
Musicus, 2022; a priori: PDI | ▲ | ▲ | ▲ | ▲ | ▲ | ▲ | ▲ | | ▲ | ▼ | FS | ▼ | M | ▼ | ▼ | | | ▲ | ▲ | ▲ | | ▼ | | | ▲ | ▼AP
Musicus, 2022; a priori: uPDI | ▼ | ▲ | ▼ | ▼ | ▲SB | ▼ | ▼ | | ▲ | ▼ | FS | ▼ | M | ▼ | ▼ | | | ▲ | ▲ | ▼ | | ▼ | | | ▼ | ▼AP
Nazari, 2018; RRR: PCR; HE:≤40% NHW | ▲ | ▲fried▲ | | | | | | | ▲ | | | ▲PR | ▲ | | | | ▲ch | | | | ▲
Nazari, 2018; RRR: PLS ; HE:≤40% NHW | ▼ | ▲fried | | | | | | | | | | ▲P | ▲ | | | | ▲ch | ▲ | ▲ | | ▲ | | | | | ▲tom
Nazari, 2018; RRR: n/a; HE:≤40% NHW | ▼ | ▲fried | ▲ | | | | | | | ▲ | | ▲P | F | F | | | | ▲ | | | ▲ | | | | | ▲tom
Neuhouser, 2023; a priori: HEI-2010 | ▲▲L | V | V, F, M | ▲▲ | | | ▲ | | ▼ | ▲pro | F (pro) | F (pro) | F (pro) | | ▲ | D | D | AS | ▼ | ▲ | | ▼ | | ▼
Noel, 2020; a priori: AHEI-2010 | ▲ | X | ▲ | ▲ | ▼ | L | ▲ | | | | | ▼RP | | | | | | ▼ | | ▲UF:SF | ▼Tr | | ◀ | ▼ | | ▲
Ogilvie, 2017; a post.: Healthy | ▲▲ | ▲ | ▲ | ▲ | ▲ | ▲ | ▲ | | ▼ | ▲ | FS | ▼P | ▲ | ▼ | ▲y | ▲ | ▲ | ▼ | ▼ | | | | | | ▲T | ▼C;▼ | ▲
Ogilvie, 2017; a post.: Western | ▼ | ▲ | ▲ | ▼ | ◀ | ▲ | ▼ | | | ▼ | FS | ▲ | | ▲ | ▼y | ▼ | ▲ | ▲ | ▲ | ▲AF | AF | AF | | | ▲ | ▲V▲ | ▼
Pang, 2021; a priori: EDIP | ▼▼ | | | | ▲ | | | | ▼ | ▼ | | ▼P▼R▼ | | | | | | ▼ | | | | | | | ▲T▲C | ▲▲▲▲
Panizza, 2018; a priori: HEI-2015; HE:≤40% NHW | ▲▲L | V | V, F, M | ▲▲ | | | ▲ | | ▼ | ▲pro | F (pro) | F (pro) | F (pro) | | ▲ | D | D | AS | ▼ | ▲UF:SF | | ▼ | | ▼
Park, 2016 IJO; a priori: MedDietScore | ▲ | ▲ | ▲ | ▲ | | | ▲ | | | ▲ | | ▼RP | ▼ | | ▼ | D | D | | ▼ | ▲UF:SF | | | ▼
Park, 2016 Mayo; a priori: HEI, 1995 | ▲ | | | ▲ | | | | ▲ | | | | ▼ | M | | ▼ | D | D | | | ▼AF | ▼ | ▼ | | ◀
Patel, 2021; a priori: AHEI | ▲ | X | ▲ | ▲ | | L | ▲ | | | | | W/R | ▲W:R | | | | | ▼ | | ▲UF:SF | | UF:SF | ◀ | | | ▲
Patel, 2021; a priori: aMED | ▲ | X | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼RP | | | | | | | | ▲UF:SF | | UF:SF | ◀
Patel, 2021; a priori: DASH | ▲ | X | ▲ | ▲ | Fr | L | ▲ | | | | | ▼RP | | | | ▲ | | ▼ | | | | | | ▼
Rai, 2023; a priori: SAM diet score; HE:≤40% NHW | ▲ | | ▲ | ▲ | | ▲ | ▲ | | | ▲ | FS | ▼RP | | | | | | | | ▲UF:SF | | UF:SF | ◀
Rebholz, 2020; a priori: AHEI-2000 | ▲ | X | ▲ | ▲ | | L | ▲ | | | | | W/R | ▲W/R | | | | | | | ▲UF:SF | ▼Tr | UF:SF | ◀ | | | ▲
Rebholz, 2020; a priori: AHEI-2010 | ▲ | X | ▲ | ▲ | SB | L | ▲ | | | | | ▼RP | | | | | | ▼ | | ▲▲ | ▼Tr | | ◀ | ▼
Rebholz, 2020; a priori: HEI-1990 | ▲ | | | ▲ | | | | ▲ | | | | ▼ | M | | ▼ | D | D | | | ▼tot. | ▼ | ▼ | | ◀ | | ▲
Rebholz, 2020; a priori: HEI-2005 | ▲▲ | V | V, M, D | ▲▲ | | | ▲ | ▲ | ▼ | | | ▲L | M, L | | ▲ | D | D | AS | ▼ | ▲ | AS, AF Alcohol | ▼ | AS, Solid, Alcohol | ▼
Rebholz, 2020; a priori: HEI-2010 | ▲▲L | V | V, F, M | ▲▲ | | | ▲ | | ▼ | ▲pro | F (pro) | F (pro) | F (pro) | | ▲ | | | AS | ▼ | ▲ | | ▼ | | ▼
Rebholz, 2020; a priori: HEI-2015 | ▲▲L | V | V, F, M | ▲▲ | | | ▲ | | ▼ | ▲pro | F (pro) | F (pro) | F (pro) | | ▲ | | | AS | ▼ | ▲UF:SF | | ▼ | | ▼
Reedy, 2014; a priori: AHEI-2010 | ▲ | X | ▲ | ▲ | SB | L | ▲ | | | | | ▼RP | | | | | | ▼ | | ▲▲ | | ▼ | | ▼
Reedy, 2014; a priori: aMED | ▲ | X | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼RP | | | | | | | | ▲UF:SF | | UF:SF | ◀
Reedy, 2014; a priori: DASH | ▲ | X | ▲ | ▲ | Fr | L | ▲ | | | | | ▼RP | | | | ▲ | | ▼ | | | | | | ▼
Reedy, 2014; a priori: HEI-2010 | ▲▲L | V | V, F, M | ▲▲ | | | ▲ | | ▼ | ▲pro | F (pro) | F (pro) | F (pro) | | ▲ | | | AS | ▼ | ▲ | | ▼ | | ▼
Reedy, 2018; a priori: HEI-2015 | ▲▲L | V | V, F, M | ▲▲ | | | ▲ | | ▼ | ▲pro | F (pro) | F (pro) | F (pro) | | ▲ | | | AS | ▼ | ▲UF:SF | | ▼ | | ▼
Santiago-Torres, 2021; a priori: aMED; HE:≤40% NHW | ▲ | X | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼RP | | | | | | | | ▲UF:SF | | UF:SF | ◀
Santiago-Torres, 2021; a priori: DASH; HE:≤40% NHW | ▲ | X | ▲ | ▲ | Fr | L | ▲ | | | | | ▼RP | | | | ▲ | | ▼ | | | | | | ▼
Santiago-Torres, 2021; a priori: HEI-2010; HE:≤40% NHW | ▲▲L | V | V, F, M | ▲▲ | | | ▲ | | ▼ | ▲pro | F (pro) | F (pro) | F (pro) | | ▲ | | | AS | ▼ | ▲ | | ▼ | | ▼
Santiago-Torres, 2021; a priori: MeDS; HE:≤40% NHW | ▲ | | ▲ | ▲ | | L | | ▲ | | ▲ | | ▲ | M | | ▲ | D | D | | | ▲UF:SF | | UF:SF | ◀
Santiago-Torres, 2021; a priori: MexD; HE:≤40% NHW | ▲ | | ▲ | ▲ | | | | ▲ | ▼ | | | ▼P | | | | | ▲ | AS | ▼ | | | ▼ | | | | ▲
Satija, 2017; a priori: hPDI | ▲ | ▼ | ▲ | ▲ | ▼ | ▲ | ▲ | | ▼ | ▼ | FS | ▼ | M | ▼ | ▼ | | | ▼ | ▲ | ▲ | | ▼ | | | ▲ | ▼AP
Satija, 2017; a priori: PDI | ▲ | ▲ | ▲ | ▲ | ▲ | ▲ | ▲ | | ▲ | ▼ | FS | ▼ | M | ▼ | ▼ | | | ▲ | ▲ | ▲ | | ▼ | | | ▲ | ▼AP
Satija, 2017; a priori: uPDI | ▼ | ▲ | ▼ | ▼ | ▲SB | ▼ | ▼ | | ▲ | ▼ | FS | ▼ | M | ▼ | ▼ | | | ▲ | ▲ | ▼ | | ▼ | | | ▼ | ▼AP
Schrauben, 2021; a priori: AHA | ▲ | | | | | | ▲ | | | ▲ | | | | | | | | ▼ | | | | | ◀ | ▼
Shah, 2018; a priori: DASH | ▲ | X | ▲ | ▲ | Fr | L | ▲ | | | | | ▼RP | | | | ▲ | | ▼ | | | | | | ▼
Shah, 2018; a priori: MDS | ▲ | | ▲ | ▲ | | ▲ | | ▲ | | ▲ | | ▼RP | | | ▼ | D | D | | | ▲UF:SF | | | ◀
Shams-White, 2022; a priori: WCRF/AICR | ▲ | | | V | | | ▲ | | | | | ▼RP | | | | | | ▼ | | | | | ◀ | | | ▼ | ▲
Shan, 2020; a priori: aMED | ▲ | X | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼RP | | | | | | | | ▲UF:SF | | UF:SF | ◀
Shan, 2020; a priori: HEI-2015 | ▲▲L | V | V, F, M | ▲▲ | | | ▲ | | ▼ | ▲pro | F (pro) | F (pro) | F (pro) | | ▲ | | | AS | ▼ | ▲UF:SF | | ▼ | | ▼
Shan, 2020; a priori: HPDI | ▲ | ▼ | ▲ | ▲ | ▼ | ▲ | ▲ | | ▼ | ▼ | FS | ▼ | M | ▼ | ▼ | | | ▼ | ▲ | ▲ | | ▼ | | | ▲ | ▼AP
Shan, 2020; a priori: AHEI-2010 | ▲ | X | ▲ | ▲ | SB | L | ▲ | | | | | ▼RP | | | | | | ▼ | | ▲▲ | | ▼ | ◀ | ▼
Shan, 2023; a priori: aMED | ▲ | X | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼RP | | | | | | | | ▲UF:SF | | UF:SF | ◀
Shan, 2023; a priori: HEI-2015 | ▲▲L | V | V, F, M | ▲▲ | | | ▲ | | ▼ | ▲pro | F (pro) | F (pro) | F (pro) | | ▲ | | | AS | ▼ | ▲UF:SF | | ▼ | | ▼
Shan, 2023; a priori: HPDI | ▲ | ▼ | ▲ | ▲ | ▼ | ▲ | ▲ | | ▼ | ▼ | FS | ▼ | M | ▼ | ▼ | | | ▼ | ▲ | ▲ | | ▼ | | | ▲ | ▼AP
Shan, 2023; a priori: AHEI-2010 | ▲ | X | ▲ | ▲ | SB | L | ▲ | | | | | ▼RP | | | | | | ▼ | | ▲▲ | | ▼ | | ▼
Shikany, 2015; a post.: Alcohol and Salad | ▲ | | | | | | | | | | | | | | | | | | | | | | ▲▲▲ | | | ▲
Shikany, 2015; a post.: Convenience | ▲ | ▲fried | ▲ | | | | | ▲ | ▲ | ▲ | FS | ▲ | ▲ | | | | ▲ | | ▲ | | | | | ▲snack foods | | ▲
Shikany, 2015; a post.: Plant-based | ▲▲▲▲ | | ▲D | ▲ | ▲100% | ▲ | ▲ | | | ▲ | | | | | ▲y | ▲ | | ▼ | | | | | ▼b | | | ▲ | ▼
Shikany, 2015; a post.: Southern | | | | | | | | | | | | ▲P▲ | | ▲ | | | | ▲ | | ▲AF | AF | AF | | | | ▲
Shikany, 2015; a post.: Sweets/Fats | | ▲▲fried | | | | | ▲ | ▲ | ▲ | | | ▲RP | | | | | ▲ | | ▲ | ▲AF | AF | ▲ | | ▲snack foods | ▲ | ▲
Shikany, 2021; Index: MDS | ▲ | | ▲ | ▲ | | ▲ | | ▲ | | ▲ | | ▼RP | | | ▼ | D | D | | | ▲UF:SF | | UF:SF | ◀
Shikany, 2021; a post.: Alcohol and Salad | ▲ | | | | | | | | | | | | | | | | | | | | | | ▲▲▲ | | | ▲
Shikany, 2021; a post.: Convenience | ▲ | | | | | | | | | | | | | | | | | | | | | | | | | ▲
Shikany, 2021; a post.: Plant-based | ▲ | | ▲ | ▲ | | | | ▲ | | ▲ | | | ▲ | | ▲y
Shikany, 2021; a post.: Southern | | | | | | | | | | | | ▲P▲ | | ▲ | | | | ▲ | | ▲AF | AF | AF | | | | ▲
Shikany, 2021; a post.: Sweets | | | | | | | | ▲ | ▲ | | | | | | | | | | ▲ | | | | | | | ▲
Shvetsov, 2016; a priori: aMED; HE:≤40% NHW | ▲ | X | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼RP | | | | | | | | ▲UF:SF | | UF:SF | ◀
Song, 2023; a priori: MIND | ▲ | ▲ | ▲ | ▲ | | ▲ | ▲ | | | | ▲ | ▼R | ▲ | | ▼ch | | | | | ▲oo | | ▼ | ▲W | | | ▼
Sotos-Prieto, 2015; a priori: AHEI-2010 | ▲ | X | ▲ | ▲ | SB | L | ▲ | | | | | ▼RP | | | | | | ▼ | | ▲▲ | ▼Tr | | ◀ | ▼
Sotos-Prieto, 2015; a priori: aMED | ▲ | X | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼RP | | | | | | | | ▲UF:SF | | UF:SF | ◀
Sotos-Prieto, 2015; a priori: DASH | ▲ | X | ▲ | ▲ | Fr | L | ▲ | | | | | ▼RP | | | | ▲ | | ▼ | | | | | | ▼
Sotos-Prieto, 2017; a priori: AHEI-2010 | ▲ | X | ▲ | ▲ | SB | L | ▲ | | | | | ▼RP | | | | | | ▼ | | ▲▲ | ▼Tr | | ◀ | ▼
Sotos-Prieto, 2017; a priori: aMED | ▲ | X | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼RP | | | | | | | | ▲UF:SF | | UF:SF | ◀
Sotos-Prieto, 2017; a priori: DASH | ▲ | X | ▲ | ▲ | Fr | L | ▲ | | | | | ▼RP | | | | ▲ | | ▼ | | | | | | ▼
Steffen, 2014; a priori: mMedDiet | ▲ | | ▲ | ▲ | ▲FrV | ▲ | ▲ | | ▼ | ▲ | | ▼RP | ▲ | ▲ | ▼ | D | D | ▼ | ▼ | ▲UF:SF | | UF:SF | ◀ | | ▲ | ▼▼▼
Tharrey, 2018; a post.: Grains | ▲ | ▲ | | | | | | ▲ | | | ▼ | | ▼ | | ▼y
Tharrey, 2018; a post.: Legumes, Fruits & Vegetables | ▲ | ▲ | ▲ | ▲ | | | | | | | | | | | ▼milk
Tharrey, 2018; a post.: Meat | | | ▼soy | | | | | ▼ | | | ▲ | ▲RP | ▲ | | ▼y
Tharrey, 2018; a post.: Nuts & Seeds | | | | | | ▲ | | | | | ▲ | | ▼ | ▼
Tharrey, 2018; a post.: Processed Foods | | ▲ | ▼Soy | | | | | | | | | | | ▲ | ▲ch | ▲milk | milk | | | | | ▲
Troeschel, 2021; a priori: ECL | ▲▲ | | | ▲ | | ▲ | | ▼ | ▼ | ▲ | | ▼RP | ▲ | | ▼ | D | D | ▼ | | | | | | ▼ | | ▲
Tsivgoulis, 2015; a priori: MDS (MeD) | ▲ | | ▲ | ▲ | | ▲ | | ▲ | | ▲ | | ▼RP | | | ▼ | D | D | | | ▲UF:SF | | | ◀
Wang P, 2023; a priori: AHEI-2010 | ▲ | X | ▲ | ▲ | SB | L | ▲ | | | | | ▼RP | | | | | | ▼ | | ▲▲ | ▼Tr | | ◀ | ▼
Wang P, 2023; a priori: aMED | ▲ | X | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼RP | | | | | | | | ▲UF:SF | | UF:SF | ◀
Wang P, 2023; a priori: DASH | ▲ | X | ▲ | ▲ | Fr | L | ▲ | | | | | ▼RP | | | | ▲ | | ▼ | | | | | | ▼
Wang P, 2023; a priori: DRRD | | | | ▲ | SB | ▲ | | | | | | ▼R | | | | | | ▼ | | ▲UF:SF | ▼Tr | UF:SF | | | ▲C | ▲ | ▼GI
Wang P, 2023; a priori: EDIH | ▲ | | | ▲ | | | | | | ▼ | | ▼RP | ▼ | ▼ | | ▼ | ▲ | ▼ | | | ▼ | | ▲ | | ▲C | ▼
Wang P, 2023; a priori: EDIP | ▼▼ | | | | ▲ | | | | ▼ | ▼ | | ▼P▼R▼ | | | | | | ▼ | | | | | | | ▲T▲C | ▲▲▲▲
Wang P, 2023; a priori: hPDI | ▲ | ▼ | ▲ | ▲ | ▼ | ▲ | ▲ | | ▼ | ▼ | FS | ▼ | M | ▼ | ▼ | | | ▼ | ▲ | ▲ | | ▼ | | | ▲ | ▼AP
Wang P, 2023; a priori: WCRF/AICR | ▲ | | | V | | | ▲ | | | | | ▼RP | | | | | | ▼ | | | | | ◀ | | | ▼ | ▲
Wang, 2020; RRR:: Western | ▼ | | | ▼ | | | ▼HF | | | ▲fried | | ▲RP | | | | | | ▲ | | | ▲ | | ▼w | | | ▼
Wang, 2020; a post.: Prudent | ▲ | | ▲ | ▲ | | | | | | | | ▼ | | | | | ▼ | | | | ▼ | | ▼b
Wang, 2020; a post.: Western | ▼ | | ▼ | ▼ | | | | | | | | ▲RP | ▲NP | | | ▼ | | | | | ▲ | | | | | ▲
Wang, 2020; a post.: Western | ▼ | ▲fried | ▼ | ▼ | | | | | | ▲fried | | ▲RP | | | | | | ▲ | | | ▲ | | | | | ▼
Wang, 2021; a priori: DRRD | | | | ▲ | SB | ▲ | | | | | | ▼R | | | | | | ▼ | | ▲UF:SF | ▼Tr | UF:SF | | | ▲C | ▲ | ▼GI
Wang, 2022; RRR: EDIH | ▼ | ▲fried | | ▼ | | | | | | ▲ | | ▲R▲P | ▲ | ▲ | | ▲ | ▼ | ▲ | | | ▲ | | ▼w | | ▼C | ▲
Wang, 2022; RRR: EDIR | ▼ | ▲fried | | ▼ | | | | | | ▲ | | ▲R▲P | ▲ | ▲ | | ▲ | ▼ | ▲ | | | ▲ | | ▼w | | ▼C | ▲
Wang, 2023; a priori: aMED | ▲ | X | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼RP | | | | | | | | ▲UF:SF | | UF:SF | ◀
Weng, 2013; a priori: HFS | ▲ | | ▲ | ▲ | X | ▲ | ▲ | | ▲ | ▲ | | ▼RP | | | | | | ▼ | | | | | ◀ | | ▲
Weston, 2022; a priori: hPDI; HE:≤40% NHW | ▲ | ▼ | ▲ | ▲ | ▼ | ▲ | ▲ | | ▼ | ▼ | FS | ▼ | M | ▼ | ▼ | | | ▼ | ▲ | ▲ | | ▼ | | | ▲ | ▼AP
Weston, 2022; a priori: PDI; HE:≤40% NHW | ▲ | ▲ | ▲ | ▲ | ▲ | ▲ | ▲ | | ▲ | ▼ | FS | ▼ | M | ▼ | ▼ | | | ▲ | ▲ | ▲ | | ▼ | | | ▲ | ▼AP
Weston, 2022; a priori: uPDI; HE:≤40% NHW | ▼ | ▲ | ▼ | ▼ | ▲SB | ▼ | ▼ | | ▲ | ▼ | FS | ▼ | M | ▼ | ▼ | | | ▲ | ▲ | ▼ | | ▼ | | | ▼ | ▼AP
Whalen, 2017; a priori: MedDietScore | ▲ | G | | ▲ | | | | ◀ | | ▲ | | ▼RP | ▲ | | ◀ | D | D | | ▼ | ▲UF:SF | | | ◀
Whalen, 2017; a priori: Paleolithic | ▲▲ | | | ▲ | | ▲ | | ▼ | ▼ | ▲ | | ▼RP | ▲ | | ▼ | D | D | | | | | | ▼ | ▼ | | ▲
Xu, 2020; a priori: AHEI-2010 | ▲ | X | ▲ | ▲ | SB | L | ▲ | | | | | ▼RP | | | | | | ▼ | | ▲▲ | ▼Tr | | ◀ | ▼
Xu, 2020; a priori: HEI-2015 | ▲▲L | V | V, F, M | ▲▲ | | | ▲ | | ▼ | ▲pro | F (pro) | F (pro) | F (pro) | | ▲ | | | AS | ▼ | ▲UF:SF | | ▼ | | ▼
Yu, 2015; a priori: HEI-2010; HE:≤40% NHW; Lower SEP | ▲▲L | V | V, F, M | ▲▲ | | | ▲ | | ▼ | ▲pro | F (pro) | F (pro) | F (pro) | | ▲ | | | AS | ▼ | ▲ | | ▼ | | ▼
Yuan, 2023; a priori: HEI-2015 | ▲▲L | V | V, F, M | ▲▲ | | | ▲ | | ▼ | ▲pro | F (pro) | F (pro) | F (pro) | | ▲ | | | AS | ▼ | ▲UF:SF | | ▼ | | ▼
Zhang, 2023; a priori: HEI-2010 | ▲▲L | V | V, F, M | ▲▲ | | | ▲ | | ▼ | ▲pro | F (pro) | F (pro) | F (pro) | | ▲ | | | AS | ▼ | ▲ | | ▼ | | ▼
Zhong VW, 2021; a priori: AHEI-2010 | ▲ | X | ▲ | ▲ | SB | L | ▲ | | | | | ▼RP | | | | | | ▼ | | ▲▲ | ▼Tr | | ◀ | ▼
Zhong, 2021; a priori: UPF, Nova4 | ▲UP | ▲ | V | | SB | | | ▲UP | | | | ▲RP | M, P | | ▲UP | ▲ | ▲ | ▲ | ▲ | ▲ | ▲ | | ▲ | ▲snack foods | SB | ▲