# Appendix 3 Inclusion and exclusion criteria comparison

Table A 3 Inclusion and exclusion criteria comparison between existing and updated systematic reviews for the research question: What is the relationship between dietary patterns consumed and risk of cardiovascular disease?

Category | Existing Review | Updated Review | Change and Rationale
Study design | [underlined: Included]:; - Randomized controlled trials; - Non-randomized controlled trials (including quasi-experimental and controlled before and after studies); - Quasi-experimental studies (i.e., prospective cohort studies); [underlined: Excluded]:; - Nested case-control studies; - Case-control studies; - Uncontrolled trials; - Case-control studies; - Cross-sectional studies; - Uncontrolled before-and-after studies; - Narrative reviews; - Systematic reviews; - Meta-analyses | [underlined: Included]:; - Randomized controlled trials; - Non-randomized controlled trials^*^; * Including quasi-experimental and controlled before-and-after studies; - Prospective cohort studies; - Retrospective cohort studies; - Nested case-control studies; [underlined: Excluded]:; - Uncontrolled trials^†^; † Including uncontrolled before-and-after studies; - Case-control studies; - Cross-sectional studies; - Ecological studies; - Narrative reviews; - Systematic reviews; - Meta-analyses; - Modeling and simulation studies; - Mendelian randomization studies | Study design criteria were modified to enable focus on the strongest body of evidence and to align with current NESR standards.
Publication date | [underlined: Included]:; - January 1980 – August 2013; [underlined: Excluded]:; - Before January 1980, after August 2013 | [underlined: Included]:; - August 2013 – October 2019/May 2023^‡^; ‡ This review update date range encompasses the original systematic review date range, which included articles published from January 1980 to August 2013; [underlined: Excluded]:; - Before August 2013, after May 2023 | End of the date range is updated to extend from the end of search in the existing review to present
Population: Study participants | [underlined: Included]:; - Human; [underlined: Excluded]:; - Non-human | [underlined: Included]:; - Human; [underlined: Excluded]:; - Non-human | No change
Population: Life stage | [underlined: Included]:; - At intervention/exposure and outcome:; ○ Children, adolescents, and adults aged 2 years and older; [underlined: Excluded]:; - At intervention/exposure and outcome:; ○ Infants and toddlers (birth up to 24 months) | [underlined: Included]:; - At intervention/exposure and outcome:; ○ Children and adolescents (2 up to 19 years); ○ Adults and older adults (19 years and older); - At intervention/exposure:; ○ Individuals during pregnancy; ○ Individuals during postpartum; [underlined: Excluded]:; - At intervention/exposure and outcome:; ○ Infants and toddlers (birth up to 24 months); - At outcome:; ○ Individuals during pregnancy; ○ Individuals during postpartum | No change
Population: Health Status | [underlined: Included]:; - Subjects who were healthy or at elevated chronic disease risk; [underlined: Excluded]:; - Low-calorie intervention (defined as <1,600 kcal/day for women and <2,000 kcal/day for men); - Subjects who were hospitalized, diagnosed with disease, and/or receiving medical treatment | [underlined: Included]:; - Studies that [underlined: exclusively] enroll participants not diagnosed with a disease^*^; * Studies that enroll participants who are at risk for chronic disease will be included; - Studies that enroll [underlined: some] participants:; ○ diagnosed with a disease;; ○ and/or hospitalized for an illness, injury, or surgery; ○ with severe undernutrition, failure to thrive/underweight, stunting, or wasting;; ○ born preterm, with low birth weight, and/or small for gestational age;; ○ pre- or post-bariatric surgery;; ○ receiving pharmacotherapy to treat obesity;; ○ and/or with the outcome of interest; [underlined: Excluded]:; - Interventions designed to induce weight loss or treat overweight and obesity through energy-restriction/hypocaloric diets for the purposes of treating additional or other medical conditions; - Studies that [underlined: exclusively] enroll participants:; ○ diagnosed with a disease;^*^; * Studies that exclusively enroll participants with obesity will be included; ○ hospitalized for an illness, injury, or surgery;^†^; † Studies that exclusively enroll participants post-cesarean section will be included; ○ with severe undernutrition, failure to thrive/underweight, stunting, or wasting;; ○ pre- or post-bariatric surgery; ○ and/or receiving pharmacotherapy to treat obesity | Population health status criteria is modified to exclude those receiving pharmacotherapy to treat obesity.
Intervention/exposure | [underlined: Included]:; - A description of the dietary pattern(s) consumed by subjects (i.e., the quantities, proportions, variety, or combination of different foods, drinks, and nutrients (when available) in diets, and the frequency with which they are habitually consumed), including, at a minimum, a description of the foods and beverages in the pattern); - Dietary patterns may be measured or derived using a variety of approaches, such as adherence to a priori patterns (indices/scores), data driven patterns (factor or cluster analysis), reduced rank regression, or other methods, including clinical trials.; [underlined: Excluded]:; - Studies that do not provide a description of the dietary pattern, which at minimum, must include the foods and beverages in the pattern (i.e., studies that examine a labeled dietary pattern, but do not describe the foods and beverages consumed). | [underlined: Included]:; - Studies that examine consumption of and/or adherence to a dietary pattern [i.e., the quantities, proportions, variety, or combination of different foods, drinks, and nutrients (when available) in diets, and the frequency with which they are habitually consumed], including, at a minimum, a description of the foods and beverages in the pattern of each intervention/exposure and comparator group; ○ Dietary patterns may be measured or derived using a variety of approaches, such as adherence to a priori patterns (indices/scores), data driven patterns (factor or cluster analysis), reduced rank regression, or other methods, including clinical trials; - Multi-component intervention in which the isolated effect of the dietary pattern on the outcome(s) of interest is provided or can be determined.; [underlined: Excluded]:; - Studies that do not provide a description of the dietary pattern, which at minimum, must include the foods and beverages in the pattern (i.e., studies that examine a labeled dietary pattern, but do not describe the foods and beverages consumed in each intervention/exposure and comparator group).; - Multi-component intervention in which the isolated effect of the dietary pattern on the outcome(s) of interest is not analyzed or cannot be determined (e.g., due to multiple intervention components within groups). | Revisions were made to clarify the intent of the intervention/exposure and comparator criteria, but do not represent a change in how the criteria were applied.
Comparator | [underlined: Included]:; - Adherence to a different dietary pattern; - Different levels of adherence to a dietary pattern; [underlined: Excluded]:; - N/A | [underlined: Included]:; - Consumption of and/or adherence to a different dietary pattern; - Different levels of consumption of and/or adherence to a dietary pattern; [underlined: Excluded]:; - Consumption of and/or adherence to a similar dietary pattern of which only a specific component or food source is different between groups | No change other than to clarify the intent.
Outcome(s) | [underlined: Included]:; - Total cholesterol; - LDL cholesterol; - HDL cholesterol, including TC:HDL and LDL:HDL ratios; - Triglycerides; - Blood pressure; - Cardiovascular disease (e.g., myocardial infarction, coronary heart disease, coronary artery disease, congestive heart failure, peripheral artery disease); - Stroke; - Venous thrombosis; - Cardiovascular disease-related mortality | [underlined: Included]:; - LDL cholesterol; - HDL cholesterol; - Triglycerides; - Hyperlipidemia; - Blood pressure (systolic, diastolic); - Hypertension; - CVD morbidity (e.g., myocardial infarction, coronary heart disease, coronary artery disease, congestive heart failure, peripheral artery disease, stroke) or composite CVD morbidity and mortality; - CVD-related mortality; [underlined: Excluded]:; - Total cholesterol; - Hypertensive disorders of pregnancy | Outcome criteria has been modified to include the most relevant outcomes
Confounders | [underlined: Included]; - n/a; [underlined: Excluded]; - n/a | [underlined: Included]:; - Studies that control for one or more of the key confounders listed in the analytic framework.; [underlined: Excluded]:; - Studies that do not control for any of the key confounders listed in the analytic framework. | Criteria were added to enable focus on a stronger body of evidence.
Study duration | [underlined: Included]; - n/a; [underlined: Excluded]; - n/a | [underlined: Included]; - Intervention length ≥4 weeks; [underlined: Excluded]; - Intervention length <4 weeks | Study duration criteria were modified to enable focus on a stronger body of evidence
Size of study groups | [underlined: Included]; - Randomized or nonrandomized controlled trial with at least 30 subjects per study arm and a follow-up rate of at least 80 percent, or a prospective cohort study; [underlined: Excluded]; - Studies with less than 30 subjects per study arm or a follow-up rate of less than 80 percent | [underlined: Included]; - For intervention studies:; ○ ≥30 participants per study group for between-subject analyses,; ○ or a power calculation indicating that the study is appropriately powered for the outcome(s) of interest; [underlined: Excluded]; - For intervention studies:; ○ <30 participants per study group for between-subject analyses,; ○ and no power calculation indicating that the study is appropriately powered for the outcome(s) of interest | Size of study groups criteria were modified to enable focus on a stronger body of evidence
Publication status | [underlined: Included]; - Peer-reviewed articles published in research journals; [underlined: Excluded]; - Non-peer reviewed articles, unpublished data or manuscripts, pre-prints, reports, and conference abstracts or proceedings | [underlined: Included]; - Peer-reviewed articles published in research journals; [underlined: Excluded]; - Non-peer reviewed articles, unpublished data or manuscripts, pre-prints, reports, and conference abstracts or proceedings | No change
Language | [underlined: Included]; - Published in English; [underlined: Excluded]; - Not published in English | [underlined: Included]; - Published in English; [underlined: Excluded]; - Not published in English | No change
Country^*^; * The classification of countries on the Human Development Index (HDI) is based on the UN Development Program Human Development Report Office (http://hdr.undp.org/en/data) for the year the study intervention occurred or data were collected. If the study does not report the year(s) in which the intervention/exposure data were collected, the HDI classification for the year of publication is applied. Studies conducted prior to 1990 are classified based on 1990 HDI classifications. If the year is more recent than the available HDI values, then the most recent HDI classifications are used. If a country is not listed in the HDI, then the current country classification from the World Bank is used ( The World Bank. World Bank country and lending groups. Available from: https://datahelpdesk.worldbank.org/knowledgebase/articles/906519-world-country-and-lending-groups ) | [underlined: Included]; - Subject populations from countries with high or very high human development, according to the 2011 Human Development Index; [underlined: Excluded]; - Studies conducted in countries classified as medium or low on the 2011 Human Development Index. | [underlined: Included]; For children and adolescents:; - Studies conducted in countries classified as high or very high on the Human Development Index the year(s) the intervention/exposure data were collected; For adults and older adults:; - Studies conducted in the U.S.; [underlined: Excluded]; For children and adolescents:; - Studies conducted in countries classified as medium or low on the Human Development Index the year(s) the intervention/exposure data were collected; For adults and older adults:; - Studies conducted outside of the U.S. | For children and adolescents, NESR now applies the Human Development Index classification from the year in which the intervention/exposure data were collected.; For adults, and older adults, the review will include studies conducted in the U.S. This decision is based on the following considerations: 1) an existing conclusion statement of strong for adults; 2) to enable focus on studies that are most applicable to the U.S. population in terms of dietary intake, risk of cardiovascular disease, and other factors that may impact the relationship being examined