# Appendix 2 Conclusion statements from the existing systematic reviews

Table A 2 Conclusion statements from the existing systematic review(s) for the research question: What is the relationship between dietary patterns consumed and risk of cardiovascular disease?

Citation | Conclusion statement and grade
Dietary Patterns Technical Expert Collaborative and NESR Staff. A Series of Systematic Reviews on the Relationship Between Dietary Patterns and Health Outcomes. March 2014. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://nesr.usda.gov/sites/default/files/201906/DietaryPatternsReport-FullFinal2.pdf (https://nesr.usda.gov/sites/default/files/2019-06/DietaryPatternsReport-FullFinal2.pdf) | There is strong and consistent evidence that in healthy adults increased adherence to dietary patterns scoring high in fruits, vegetables, whole grains, nuts, legumes, unsaturated oils, low-fat dairy, poultry and fish; low in red and processed meat, high-fat dairy, and added sugars; and moderate in alcohol is associated with decreased risk of fatal and non-fatal cardiovascular diseases, including coronary heart disease and stroke. (Grade: Strong); Limited evidence from epidemiological studies indicates that dietary patterns, assessed using cluster or factor analysis, characterized by vegetables, fruits, whole grains, fish, and low-fat dairy products are associated with decreased risk of cardiovascular disease in adults. Evidence of a relationship between dietary patterns characterized by red and processed meat, sugar-sweetened foods and drinks, and fried foods and an increased risk of cardiovascular disease is limited and less consistent. (Grade: III-Limited).; Insufficient evidence, due to a small number of studies, was available to examine the relationship between dietary patterns derived using reduced rank regression and risk of cardiovascular disease. The disparate nature of the methods used made it difficult to compare results, and therefore, no conclusions were drawn. (Grade: Not Assignable); There is strong and consistent evidence that consumption of a DASH diet results in reduced blood pressure in adults with above optimal blood pressure, up to and including stage 1 hypertension. A dietary pattern consistent with the DASH diet is rich in fruits, vegetables, low-fat dairy, fish, whole grains, fiber, potassium, and other minerals at recommended levels and low in red and processed meat, sugar-sweetened foods and drinks, saturated fat, cholesterol, and sodium. There is limited evidence that adherence to vegetarian diets is associated with decreased death from ischemic heart disease, with the association being stronger in men than in women. (Grade: Strong - DASH and Blood Pressure; Grade: Limited – Vegetarian and Ischemic Heart Disease)
Boushey C, Ard J, Bazzano L, Heymsfield S, Mayer-Davis E, Sabaté J, Snetselaar L, Van Horn L, Schneeman B, English LK, Bates M, Callahan E, Butera G, Terry N, Obbagy J. Dietary Patterns and Risk of Cardiovascular Disease: A Systematic Review. July 2020. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: | Limited evidence suggests that dietary patterns consumed by children and adolescents reflecting higher intakes of vegetables, fruits, whole grains, fish, low-fat dairy, legumes, and lower intake of sugar-sweetened beverages, other sweets, and processed meat, are associated with lower blood pressure and blood lipid levels, including low-density lipoprotein cholesterol, high-density lipoprotein cholesterol, and triglycerides later in life. (Grade: Limited); The 2020 Dietary Guidelines Advisory Committee conducted a systematic evidence scan and confirmed that the conclusion drawn by the 2015 Dietary Guidelines Advisory Committee generally reflects the current state of science: Strong and consistent evidence demonstrates that dietary patterns associated with decreased risk of cardiovascular disease are characterized by higher consumption of vegetables, fruits, whole grains, low-fat dairy, and seafood, and lower consumption of red and processed meat, and lower intakes of refined grains, and sugar-sweetened foods and beverages relative to less healthy patterns. Regular consumption of nuts and legumes and moderate consumption of alcohol also are shown to be components of a beneficial dietary pattern in most studies. Randomized dietary intervention studies have demonstrated that healthy dietary patterns exert clinically meaningful impact on cardiovascular risk factors, including blood lipids and blood pressure. Additionally, research that includes specific nutrients in their description of dietary patterns indicate that patterns that are lower in saturated fat, cholesterol, and sodium and richer in fiber, potassium, and unsaturated fats are beneficial for reducing cardiovascular disease risk. (2015 Dietary Guidelines Advisory Committee Grade: Strong)