# Appendix 1 Abbreviations

Table A 1 List of abbreviations

Abbreviation | Full name
AAPI | Asian American Pacific Islander
aMED | Alternate Mediterranean Diet Score
AHEI | Alternative Healthy Eating Index
BMI | Body mass index
CABG | Coronary artery bypass graft
CDQS | Child Diet Quality Score
CHD | Coronary Heart Disease
CVD | Cardiovascular Disease
DBP | Diastolic Blood Pressure
DGI-CA | Dietary Guideline Index for Children and Adolescents
DP | Dietary pattern
EDIH | Empirically dietary indices for hyperinsulinemia
EDIR | Empirical dietary indices for insulin resistance
FFQ | Food frequency questionnaire
HDL-C | High-density lipoprotein
HDI | Human Development Index
HEI | Healthy Eating Index
HHS | United States Department of Health and Human Services
LDL-C | Low-density lipoprotein
MED | Mediterranean-Style
MI | Myocardial Infarction
NESR | Nutrition Evidence Systematic Review
NHB | Non-Hispanic Black
NHW | Non-Hispanic White
PCS | Prospective cohort study
PDI | Plant-based Diet Index
RCT | Randomized controlled trial
SBP | Systolic Blood Pressure
SEP | Socioeconomic position
TEI | Total energy intake
TG | Triglyceride
USDA | United States Department of Agriculture
UPF | Ultra-processed food