# References of included articles in the systematic review

1 Asoudeh F, Fallah M, Aminianfar A, . The effect of Mediterranean diet on inflammatory biomarkers and components of metabolic syndrome in adolescent girls. J Endocrinol Invest. Oct 2023;46(10):1995–2004. doi:10.1007/s40618-023-02027-1 36795242
2 Aljahdali AA, Peterson KE, Cantoral A, . Diet Quality Scores and Cardiometabolic Risk Factors in Mexican Children and Adolescents: A Longitudinal Analysis. Nutrients. Feb 20 2022;14(4)doi:10.3390/nu14040896
3 Asghari G, Yuzbashian E, Mirmiran P, Hooshmand F, Najafi R, Azizi F. Dietary Approaches to Stop Hypertension (DASH) Dietary Pattern Is Associated with Reduced Incidence of Metabolic Syndrome in Children and Adolescents. J Pediatr. Jul 2016;174:178–184.e1. doi:10.1016/j.jpeds.2016.03.077 27156186
4 Buckland G, Taylor CM, Emmett PM, Johnson L, Northstone K. Prospective association between a Mediterranean-style dietary score in childhood and cardiometabolic risk in young adults from the ALSPAC birth cohort. Eur J Nutr. Mar 2022;61(2):737–752. doi:10.1007/s00394-021-02652-7 34532761
5 Bull CJ, Northstone K. Childhood dietary patterns and cardiovascular risk factors in adolescence: results from the Avon Longitudinal Study of Parents and Children (ALSPAC) cohort. Public Health Nutr. Dec 2016;19(18):3369–3377.27339189
6 Chan She Ping-Delfos WL, Beilin LJ, Oddy WH, Burrows S, Mori TA. Use of the Dietary Guideline Index to assess cardiometabolic risk in adolescents. Br J Nutr. Jun 14 2015;113(11):1741–52.25873301
7 Costa JP, Magalhaes V, Araujo J, Ramos E. A lower energy intake contributes to a better cardiometabolic profile in adolescence: Data from the EPITeen cohort. Nutr Res. Mar 2023;111:14–23. doi:10.1016/j.nutres.2023.01.002 36791661
8 Durao C, Severo M, Oliveira A, Lopes C. Sex-Heterogeneity on the Association between Dietary Patterns at 4 Years of Age with Adiposity and Cardiometabolic Risk Factors at 10 Years of Age. Article. Nutrients. Jan 26 2022;14(3)doi:10.3390/nu14030540
9 Krijger JA, Nicolaou M, Nguyen AN, Voortman T, Hutten BA, Vrijkotte TG. Diet quality at age 5-6 and cardiovascular outcomes in preadolescents. Clin Nutr ESPEN. 2021;43doi:10.1016/j.clnesp.2021.02.011
10 Luque V, Closa-Monasterolo R, Grote V, . Dietary Patterns Acquired in Early Life are Associated with Cardiometabolic Markers at School Age. Clin Nutr. Jul 2021;40(7):4606–4614.34229265
11 McCourt HJ, Draffin CR, Woodside JV, . Dietary patterns and cardiovascular risk factors in adolescents and young adults: the Northern Ireland Young Hearts Project. Br J Nutr. Nov 28 2014;112(10):1685–98. doi:10.1017/s0007114514002682 25234582
12 Pinto A, Santos AC, Lopes C, Oliveira A. Dietary patterns at 7 year-old and their association with cardiometabolic health at 10 year-old. Clin Nutr. May 10 2019;
13 Siddiqui NZ, Nguyen AN, Santos S, Voortman T. Diet quality and cardiometabolic health in childhood: the Generation R Study. Eur J Nutr. Mar 2022;61(2):729–736. doi:10.1007/s00394-021-02673-2 34528119
14 Vallejo RM, Schulz CA, van de Locht K, Oluwagbemigun K, Alexy U, Nöthlings U. Associations Between Adherence to a Dietary Index Based on the EAT-Lancet Reference Diet with Nutritional, Anthropometric and Ecological Sustainability Parameters: Results From the German DONALD Cohort Study. J Nutr. 2022;doi:10.1093/jn/nxac094
15 Wu F, Pahkala K, Juonala M, . Dietary Pattern Trajectories from Youth to Adulthood and Adult Risk of Impaired Fasting Glucose: A 31-year Cohort Study. Article. Journal of Clinical Endocrinology and Metabolism. 2021;106(5):E2078–E2086. doi:10.1210/clinem/dgab044 33507261
16 Babio N, Toledo E, Estruch R, . Mediterranean diets and metabolic syndrome status in the PREDIMED randomized trial. CMAJ. Nov 18 2014;186(17):E649–57. doi:10.1503/cmaj.140764 25316904
17 Bruno E, Oliverio A, Paradiso AV, . A Mediterranean Dietary Intervention in Female Carriers of BRCA Mutations: Results from an Italian Prospective Randomized Controlled Trial. Cancers (Basel). Dec 11 2020;12(12)doi:10.3390/cancers12123732
18 Calvo-Malvar M, Benitez-Estevez AJ, Sanchez-Castro J, Leis R, Gude F. Effects of a Community-Based Behavioral Intervention with a Traditional Atlantic Diet on Cardiometabolic Risk Markers: A Cluster Randomized Controlled Trial ("The GALIAT Study"). Nutrients. Apr 7 2021;13(4)
19 Georgoulis M, Yiannakouris N, Kechribari I, . Sustained improvements in the cardiometabolic profile of patients with obstructive sleep apnea after a weight-loss Mediterranean diet/lifestyle intervention: 12-month follow-up (6 months post-intervention) of the “MIMOSA” randomized clinical trial. Nutr Metab Cardiovasc Dis. May 2023;33(5):1019–1028. doi:10.1016/j.numecd.2023.02.010 36958969
20 Georgoulis M, Yiannakouris N, Kechribari I, . The effectiveness of a weight-loss Mediterranean diet/lifestyle intervention in the management of obstructive sleep apnea: Results of the “MIMOSA” randomized clinical trial. Clin Nutr. Mar 2021;40(3):850–859.32928580
21 Georgoulis M, Yiannakouris N, Kechribari I, . Cardiometabolic Benefits of a Weight-Loss Mediterranean Diet/Lifestyle Intervention in Patients with Obstructive Sleep Apnea: The “MIMOSA” Randomized Clinical Trial. Nutrients. May 28 2020;12(6)
22 Gotfredsen JL, Hoppe C, Andersen R, . Effects of substitution dietary guidelines targeted at prevention of IHD on dietary intake and risk factors in middle-aged Danish adults: the Diet and Prevention of Ischemic Heart Disease: a Translational Approach (DIPI) randomised controlled trial. Br J Nutr. Oct 28 2021;126(8):1179–1193. doi:10.1017/s0007114520005164 33357247
23 Howard BV, Aragaki AK, Tinker LF, . A Low-Fat Dietary Pattern and Diabetes: A Secondary Analysis From the Women’s Health Initiative Dietary Modification Trial. Diabetes Care. Apr 2018;41(4):680–687.29282203
24 Pavić E, Hadžiabdić MO, Mucalo I, . Effect of the Mediterranean diet in combination with exercise on metabolic syndrome parameters: 1-year randomized controlled trial. Journal Article; Randomized Controlled Trial. International journal for vitamin and nutrition research. 2019;89(3–4):132–143.31322480
25 Prentice RL, Aragaki AK, Howard BV, . Low-Fat Dietary Pattern among Postmenopausal Women Influences Long-Term Cancer, Cardiovascular Disease, and Diabetes Outcomes. Journal Article; Randomized Controlled Trial; Research Support, N.I.H., Extramural. Journal of nutrition. 2019;149(9):1565–1574.31175807
26 Reidlinger DP, Darzi J, Hall WL, Seed PT, Chowienczyk PJ, Sanders TA. How effective are current dietary guidelines for cardiovascular disease prevention in healthy middle-aged and older men and women? A randomized controlled trial. Am J Clin Nutr. May 2015;101(5):922–30.25787998
27 Salas-Salvado J, Bullo M, Estruch R, . Prevention of diabetes with Mediterranean diets: a subgroup analysis of a randomized trial. Ann Intern Med. Jan 7 2014;160(1):1–10.
28 Sidahmed E, Cornellier ML, Ren J, . Development of exchange lists for Mediterranean and Healthy Eating diets: implementation in an intervention trial. J Hum Nutr Diet. Oct 2014;27(5):413–25.24112099
29 Tussing-Humphreys L, Lamar M, McLeod A, . Effect of Mediterranean diet and Mediterranean diet plus calorie restriction on cognition, lifestyle, and cardiometabolic health: A randomized clinical trial. Article. Preventive Medicine Reports. 2022;29doi:10.1016/j.pmedr.2022.101955
30 Ahmad S, Moorthy MV, Demler OV, . Assessment of Risk Factors and Biomarkers Associated With Risk of Cardiovascular Disease Among Women Consuming a Mediterranean Diet. JAMA Netw Open. Dec 7 2018;1(8):e185708.30646282
31 Ahmad S, Demler OV, Sun Q, . Association of the Mediterranean Diet With Onset of Diabetes in the Women’s Health Study. JAMA Netw Open. Nov 2 2020;3(11):e2025466.33211107
32 Alae-Carew C, Scheelbeek P, Carrillo-Larco RM, Bernabe-Ortiz A, Checkley W, Miranda JJ. Analysis of dietary patterns and cross-sectional and longitudinal associations with hypertension, high BMI and type 2 diabetes in Peru. Public Health Nutr. Apr 2020;23(6):1009–1019.31456536
33 Alhazmi A, Stojanovski E, McEvoy M, Brown W, Garg ML. Diet quality score is a predictor of type 2 diabetes risk in women: the Australian Longitudinal Study on Women’s Health. Br J Nutr. Sep 28 2014;112(6):945–51.25201303
34 Allaire BT, Tjaden AH, Venditti EM, . Diet quality, weight loss, and diabetes incidence in the Diabetes Prevention Program (DPP). BMC Nutr. Dec 15 2020;6(1):74.33317629
35 André P, Proctor G, Driollet B, . The role of overweight in the association between the Mediterranean diet and the risk of type 2 diabetes mellitus: a mediation analysis among 21 585 UK biobank participants. Int J Epidemiol. Oct 1 2020;49(5):1582–1590. doi:10.1093/ije/dyaa103 32754745
36 Bantle AE, Chow LS, Steffen LM, . Association of Mediterranean diet and cardiorespiratory fitness with the development of pre-diabetes and diabetes: the Coronary Artery Risk Development in Young Adults (CARDIA) study. BMJ Open Diabetes Res Care. 2016;4(1):e000229.
37 Bao W, Li S, Chavarro JE, . Low Carbohydrate-Diet Scores and Long-term Risk of Type 2 Diabetes Among Women With a History of Gestational Diabetes Mellitus: A Prospective Cohort Study. Diabetes Care. Jan 2016;39(1):43–9.26577416
38 Beigrezaei S, Jambarsang S, Khayyatzadeh SS, Mirzaei M, Mehrparvar AH, Salehi-Abargouei A. The association between dietary patterns derived by three statistical methods and type 2 diabetes risk: YaHS-TAMYZ and Shahedieh cohort studies. Scientific Reports. Jan 9 2023;13(1)doi:ARTN 410 10.1038/s41598-023-27645-w
39 Boonpor J, Petermann-Rocha F, Parra-Soto S, . Types of Diet, Obesity, and Incident Type 2 Diabetes: Findings from The UK Biobank Prospective Cohort Study. 2022;
40 Brayner B, Kaur G, Keske MA, Perez-Cornago A, Piernas C, Livingstone KM. Dietary Patterns Characterized by Fat Type in Association with Obesity and Type 2 Diabetes: A Longitudinal Study of UK Biobank Participants. J Nutr. Nov 2 2021;151(11):3570–3578. doi:10.1093/jn/nxab275 34522964
41 Cea-Soriano L, Pulido J, Franch-Nadal J, . Mediterranean diet and diabetes risk in a cohort study of individuals with prediabetes: propensity score analyses. Diabet Med. Jun 2022;39(6):e14768. doi:10.1111/dme.14768 34897805
42 Cespedes EM, Hu FB, Tinker L, . Multiple Healthful Dietary Patterns and Type 2 Diabetes in the Women’s Health Initiative. Am J Epidemiol. Apr 1 2016;183(7):622–33.26940115
43 Chen GC, Koh WP, Neelakantan N, Yuan JM, Qin LQ, van Dam RM. Diet Quality Indices and Risk of Type 2 Diabetes Mellitus: The Singapore Chinese Health Study. Am J Epidemiol. Dec 1 2018;187(12):2651–2661.30165478
44 Chen Z, Zuurmond MG, van der Schaft N, . Plant versus animal based diets and insulin resistance, prediabetes and type 2 diabetes: the Rotterdam Study. Eur J Epidemiol. Sep 2018;33(9):883–893.29948369
45 Chen Z, Drouin-Chartier J-P, Li Y, . Changes in Plant-Based Diet Indices and Subsequent Risk of Type 2 Diabetes in Women and Men: Three U.S. Prospective Cohorts. Diabetes Care. 2021;44(3):663–671.33441419
46 Choi Y, Larson N, Gallaher DD, . A Shift Toward a Plant-Centered Diet From Young to Middle Adulthood and Subsequent Risk of Type 2 Diabetes and Weight Gain: The Coronary Artery Risk Development in Young Adults (CARDIA) Study. Diabetes Care. Nov 2020;43(11):2796–2803.32847828
47 Choi Y, Jacobs DR, Bancks MP, . Association of Cardiovascular Health Score With Early- and Later-Onset Diabetes and With Subsequent Vascular Complications of Diabetes. J Am Heart Assoc. Jan 3 2023;12(1):e027558. doi:10.1161/JAHA.122.027558 36565184
48 Conway BN, Han X, Munro HM, . The obesity epidemic and rising diabetes incidence in a low-income racially diverse southern US cohort. PLoS One. 2018;13(1):e0190993. doi:10.1371/journal.pone.0190993 29324894
49 den Braver NR, Rutters F, van der Spek A, . Adherence to a food group-based dietary guideline and incidence of prediabetes and type 2 diabetes. Eur J Nutr. Aug 2020;59(5):2159–2169. doi:10.1007/s00394-01902064-8 31342227
50 Dominguez LJ, Bes-Rastrollo M, Basterra-Gortari FJ, Gea A, Barbagallo M, Martinez-Gonzalez MA. Association of a Dietary Score with Incident Type 2 Diabetes: The Dietary-Based Diabetes-Risk Score (DDS). PLoS One. 2015;10(11):e0141760.26544985
51 Dow C, Balkau B, Bonnet F, . Strong adherence to dietary and lifestyle recommendations is associated with decreased type 2 diabetes risk in the AusDiab cohort study. Prev Med. Jun 2019;123:208–216.30851294
52 Duan MJ, Dekker LH, Carrero JJ, Navis G. Lifestyle patterns and incident type 2 diabetes in the Dutch lifelines cohort study. Article. Preventive Medicine Reports. 2022;30doi:10.1016/j.pmedr.2022.102012
53 Duan MJ, Dekker LH, Carrero JJ, Navis G. Blood lipids-related dietary patterns derived from reduced rank regression are associated with incident type 2 diabetes. Clin Nutr. Jul 2021;40(7):4712–4719.34237698
54 Duan MJ, Vinke PC, Navis G, Corpeleijn E, Dekker LH. Ultra-processed food and incident type 2 diabetes: studying the underlying consumption patterns to unravel the health effects of this heterogeneous food category in the prospective Lifelines cohort. BMC Med. Jan 13 2022;20(1):7. doi:10.1186/s12916-021-02200-4 35022060
55 Eguaras S, Bes-Rastrollo M, Ruiz-Canela M, Carlos S, e la Rosa P, Martinez-Gonzalez MA. May the Mediterranean diet attenuate the risk of type 2 diabetes associated with obesity: the Seguimiento Universidad de Navarra (SUN) cohort. Br J Nutr. May 2017;117(10):1478–1485.28625175
56 Ericson U, Hindy G, Drake I, . Dietary and genetic risk scores and incidence of type 2 diabetes. Genes Nutr. 2018;13:13.29796113
57 Ericson U, Brunkwall L, Alves Dias J, . Food patterns in relation to weight change and incidence of type 2 diabetes, coronary events and stroke in the Malmö Diet and Cancer cohort. Article. European Journal of Nutrition. 2019;58(5):1801–1814.29855685
58 Esfandiar Z, Hosseini-Esfahani F, Mirmiran P, Azizi F. Diet quality indices and the risk of type 2 diabetes in the Tehran Lipid and Glucose Study. BMJ Open Diabetes Res Care. Sep 2022;10(5)doi:10.1136/bmjdrc-2022-002818
59 Farhadnejad H, Mokhtari E, Teymoori F, . Association of the insulinemic potential of diet and lifestyle with risk of diabetes incident in Tehranian adults: a population based cohort study. Nutr J. Apr 23 2021;20(1):39. doi:10.1186/s12937-021-00697-2 33892738
60 Filippatos TD, Panagiotakos DB, Georgousopoulou EN, . Mediterranean Diet and 10-year (2002-2012) Incidence of Diabetes and Cardiovascular Disease in Participants with Prediabetes: The ATTICA study. Rev Diabet Stud. Winter 2016;13(4):226–235.28278309
61 Freisling H, Viallon V, Lennon H, . Lifestyle factors and risk of multimorbidity of cancer and cardiometabolic diseases: a multinational cohort study. BMC Med. Jan 10 2020;18(1):5.31918762
62 Fung TT, Li Y, Bhupathiraju SN, . Higher Global Diet Quality Score Is Inversely Associated with Risk of Type 2 Diabetes in US Women. J Nutr. Oct 23 2021;151(12 Suppl 2):168s–175s. doi:10.1093/jn/nxab195 34689196
63 Galbete C, Kroger J, Jannasch F, . Nordic diet, Mediterranean diet, and the risk of chronic diseases: the EPIC-Potsdam study. BMC Med. Jun 27 2018;16(1):99.29945632
64 Gao M, Jebb SA, Aveyard P, . Associations Between Dietary Patterns and Incident Type 2 Diabetes: Prospective Cohort Study of 120,343 UK Biobank Participants. Diabetes Care. Jun 2022;45(6):1315–1325. doi:10.2337/dc21-2258 35299247
65 Glenn AJ, Li J, Lo K, . The Portfolio Diet and Incident Type 2 Diabetes: Findings From the Women’s Health Initiative Prospective Cohort Study. Diabetes Care. Jan 1 2023;46(1):28–37. doi:10.2337/dc22-1029 36162007
66 Glenn AJ, Hernandez-Alonso P, Kendall CWC, . Longitudinal changes in adherence to the portfolio and DASH dietary patterns and cardiometabolic risk factors in the PREDIMED-Plus study. Clin Nutr. May 2021;40(5):2825–2836. doi:10.1016/j.clnu.2021.03.016 33933749
67 Hirahatake KM, Jacobs DR, Jr S, J. M J, L W, N. D O. Cumulative average dietary pattern scores in young adulthood and risk of incident type 2 diabetes: the CARDIA study. Diabetologia. Sep 2 2019;
68 Hlaing-Hlaing H, Dolja-Gore X, Tavener M, James EL, Hure AJ. Alternative Healthy Eating Index-2010 and Incident Non-Communicable Diseases: Findings from a 15-Year Follow Up of Women from the 1973–78 Cohort of the Australian Longitudinal Study on Women’s Health. Article. Nutrients. 2022;14(20)doi:10.3390/nu14204403
69 Hlaing-Hlaing H, Dolja-Gore X, Tavener M, James EL, Hodge AM, Hure AJ. Diet quality and incident non-communicable disease in the 1946–1951 cohort of the australian longitudinal study on women’s health. Article. International Journal of Environmental Research and Public Health. 2021;18(21)
70 Hodge AM, Karim MN, Hebert JR, Shivappa N, de Courten B. Association between Diet Quality Indices and Incidence of Type 2 Diabetes in the Melbourne Collaborative Cohort Study. Nutrients. Nov 20 2021;13(11)doi:10.3390/nu13114162
71 Jacobs S, Harmon BE, Boushey CJ, . A priori-defined diet quality indexes and risk of type 2 diabetes: the Multiethnic Cohort. Diabetologia. Jan 2015;58(1):98–112.25319012
72 Jacobs S, Boushey CJ, Franke AA, . A priori-defined diet quality indices, biomarkers and risk for type 2 diabetes in five ethnic groups: the Multiethnic Cohort. Br J Nutr. Aug 2017;118(4):312–320.28875870
73 Jacobs S, Kroeger J, Schulze MB, . Dietary Patterns Derived by Reduced Rank Regression Are Inversely Associated with Type 2 Diabetes Risk across 5 Ethnic Groups in the Multiethnic Cohort. Curr Dev Nutr. May 2017;1(5):e000620.29955702
74 Jannasch F, Kroger J, Agnoli C, . Generalizability of a Diabetes-Associated Country-Specific Exploratory Dietary Pattern Is Feasible Across European Populations. J Nutr. Jun 1 2019;149(6):1047–1055.31149710
75 Jin Q, Shi N, Aroke D, . Insulinemic and Inflammatory Dietary Patterns Show Enhanced Predictive Potential for Type 2 Diabetes Risk in Postmenopausal Women. Diabetes Care. Mar 2021;44(3):707–714.33419931
76 Kanerva N, Rissanen H, Knekt P, Havulinna AS, Eriksson JG, Mannisto S. The healthy Nordic diet and incidence of Type 2 Diabetes-10-year follow-up. Diabetes Res Clin Pract. Nov 2014;106(2):e34–7.25245974
77 Kesse-Guyot E, Chaltiel D, Fezeu LK, . Association between adherence to the French dietary guidelines and the risk of type 2 diabetes. Nutrition. Apr 2021;84:111107.33454528
78 Khalili-Moghadam S, Mirmiran P, Bahadoran Z, Azizi F. The Mediterranean diet and risk of type 2 diabetes in Iranian population. Eur J Clin Nutr. Jan 2019;73(1):72–78.30315315
79 Kim J, Giovannucci E. Healthful Plant-Based Diet and Incidence of Type 2 Diabetes in Asian Population. Nutrients. Jul 27 2022;14(15)doi:10.3390/nu14153078
80 Koloverou E, Panagiotakos DB, Pitsavos C, . Adherence to Mediterranean diet and 10-year incidence (2002-2012) of diabetes: correlations with inflammatory and oxidative stress biomarkers in the ATTICA cohort study. Diabetes Metab Res Rev. Jan 2016;32(1):73–81.26104243
81 Koloverou E, Panagiotakos DB, Georgousopoulou EN, . Dietary Patterns and 10-year (2002-2012) Incidence of Type 2 Diabetes: Results from the ATTICA Cohort Study. Rev Diabet Stud. Winter 2016;13(4):246–256.28394951
82 InterActConsortium. Adherence to predefined dietary patterns and incident type 2 diabetes in European populations: EPIC-InterAct Study. Diabetologia. Feb 2014;57(2):321–33. doi:10.1007/s00125-013-3092-9 24196190
83 Lacoppidan SA, Kyro C, Loft S, . Adherence to a Healthy Nordic Food Index Is Associated with a Lower Risk of Type-2 Diabetes-The Danish Diet, Cancer and Health Cohort Study. Nutrients. Oct 21 2015;7(10):8633–44.26506373
84 Langmann F, Ibsen DB, Tjønneland A, Olsen A, Overvad K, Dahm CC. Adherence to the EAT-Lancet diet is associated with a lower risk of type 2 diabetes: the Danish Diet, Cancer and Health cohort. Eur J Nutr. Apr 2023;62(3):1493–1502. doi:10.1007/s00394-023-03090-3 36688993
85 Laouali N, Shah S, Macdonald CJ, . BMI in the Associations of Plant-Based Diets with Type 2 Diabetes and Hypertension Risks in Women: The E3N Prospective Cohort Study. Article. Journal of Nutrition. 2021;151(9):2731–2740. doi:10.1093/jn/nxab158 34236437
86 Lee HA, Son N, Lee WK, Park H. A Diabetes-Related Dietary Pattern Is Associated with Incident Diabetes in Obese Men in the Korean Genome Epidemiology Study. J Nutr. Feb 1 2019;149(2):323–329.30590687
87 Lee KW, Woo HD, Cho MJ, Park JK, Kim SS. Identification of Dietary Patterns Associated with Incidence of Hyperglycemia in Middle-Aged and Older Korean Adults. Nutrients. Aug 4 2019;11(8)doi:10.3390/nu11081801
88 Lee DH, Li J, Li Y, . Dietary Inflammatory and Insulinemic Potential and Risk of Type 2 Diabetes: Results From Three Prospective U.S. Cohort Studies. Diabetes Care. Nov 2020;43(11):2675–2683.32873589
89 Ley SH, Pan A, Li Y, . Changes in Overall Diet Quality and Subsequent Type 2 Diabetes Risk: Three U.S. Prospective Cohorts. Diabetes Care. Nov 2016;39(11):2011–2018.27634391
90 Llavero-Valero M, Escalada-San Martín J, Martínez-González MA, Basterra-Gortari FJ, e la Fuente-Arrillaga C, Bes-Rastrollo M. Ultra-processed foods and type-2 diabetes risk in the SUN project: A prospective cohort study. Article. Clinical Nutrition. 2021;40(5):2817–2824. doi:10.1016/j.clnu.2021.03.039 33933748
91 López GE, Batis C, González C, . EAT-Lancet Healthy Reference Diet score and diabetes incidence in a cohort of Mexican women. Eur J Clin Nutr. Mar 2023;77(3):348–355. doi:10.1038/s41430-022-01246-8 36471166
92 Ma E, Ohira T, Hirai H, . Dietary Patterns and New-Onset Type 2 Diabetes Mellitus in Evacuees after the Great East Japan Earthquake: A 7-Year Longitudinal Analysis in the Fukushima Health Management Survey. Nutrients. Nov 17 2022;14(22)doi:10.3390/nu14224872
93 Maldonado LE, Sotres-Alvarez D, Mattei J, . A Posteriori dietary patterns, insulin resistance, and diabetes risk by Hispanic/Latino heritage in the HCHS/SOL cohort. Nutr Diabetes. Oct 13 2022;12(1):44. doi:10.1038/s41387-022-00221-3 36229451
94 Mandalazi E, Drake I, Wirfält E, Orho-Melander M, Sonestedt E. A high diet quality based on dietary recommendations is not associated with lower incidence of type 2 diabetes in the malmö diet and cancer cohort. Article. International Journal of Molecular Sciences. 2016;17(6)
95 Markanti L, Ibsen DB, Tjønneland A, Overvad K, Dahm CC. Adherence to the Danish food-based dietary guidelines and risk of type 2 diabetes: the Danish diet, cancer, and health cohort. Article. European Journal of Clinical Nutrition. 2021;75(5):836–844. doi:10.1038/s41430-020-00805-1 33191404
96 Mattei J, Sotos-Prieto M, Bigornia SJ, Noel SE, Tucker KL. The Mediterranean Diet Score Is More Strongly Associated with Favorable Cardiometabolic Risk Factors over 2 Years Than Other Diet Quality Indexes in Puerto Rican Adults. J Nutr. Apr 2017;147(4):661–669.28275099
97 Merino J, Guasch-Ferre M, Li J, . Polygenic scores, diet quality, and type 2 diabetes risk: An observational study among 35,759 adults from 3 US cohorts. PLoS Med. Apr 2022;19(4):e1003972. doi:10.1371/journal.pmed.1003972 35472203
98 Neuhouser ML, Pettinger M, Tinker LF, . Associations of Biomarker-Calibrated HEI-2010 Scores With Chronic Disease Risk and Their Dependency On Energy Intake and Body Mass Index in Postmenopausal Women. 2023;
99 O’Connor LE, Hu EA, Steffen LM, Selvin E, Rebholz CM. Adherence to a Mediterranean-style eating pattern and risk of diabetes in a U.S. prospective cohort study. Nutr Diabetes. Mar 20 2020;10(1):8.32198350
100 Otto MC, Padhye NS, Bertoni AG, Jacobs DR, Jr., Mozaffarian D. Everything in Moderation-Dietary Diversity and Quality, Central Obesity and Risk of Diabetes. PLoS One. 2015;10(10):e0141341. doi:10.1371/journal.pone.0141341 26517708
101 Pant A, Gribbin S, Machado P, . Ultra-processed foods and incident cardiovascular disease and hypertension in middle-aged women. Eur J Nutr. Apr 2024;63(3):713–725. doi:10.1007/s00394-023-03297-4 38147150
102 Papier K, Appleby PN, Fensom GK, . Vegetarian diets and risk of hospitalisation or death with diabetes in British adults: results from the EPIC-Oxford study. Nutr Diabetes. Feb 25 2019;9(1):7.30804320
103 Pastorino S, Richards M, Pierce M, Ambrosini GL. A high-fat, high-glycaemic index, low-fibre dietary pattern is prospectively associated with type 2 diabetes in a British birth cohort. Br J Nutr. May 2016;115(9):1632–42.27245103
104 Qiao Y, Tinker L, Olendzki BC, . Racial/ethnic disparities in association between dietary quality and incident diabetes in postmenopausal women in the United States: the Women’s Health Initiative 1993-2005. Ethn Health. Jun 2014;19(3):328–47.23697968
105 Rajaobelina K, Dow C, Romana Mancini F, . Population attributable fractions of the main type 2 diabetes mellitus risk factors in women: Findings from the French E3N cohort. Article. Journal of Diabetes. 2019;11(3):242–253.30098121
106 Rayner J, D’Arcy E, Ross LJ, Hodge A, Schoenaker D. Carbohydrate restriction in midlife is associated with higher risk of type 2 diabetes among Australian women: A cohort study. Nutr Metab Cardiovasc Dis. Mar 9 2020;30(3):400–409.31822429
107 Riboldi BP, Luft VC, Bracco PA, . The inflammatory food index and its association with weight gain and incidence of diabetes: Longitudinal Study of Adult Health (ELSA-Brasil). Nutr Metab Cardiovasc Dis. 2022;doi:10.1016/j.numecd.2021.12.022
108 Ruiz-Estigarribia L, Martinez-Gonzalez MA, Diaz-Gutierrez J, Sayon-Orea C, Basterra-Gortari FJ, Bes-Rastrollo M. Lifestyle behavior and the risk of type 2 diabetes in the Seguimiento Universidad de Navarra (SUN) cohort. Nutr Metab Cardiovasc Dis. Jul 24 2020;30(8):1355–1364.32546389
109 Sali S, Farhadnejad H, Asghari G, . Animal based low carbohydrate diet is associated with increased risk of type 2 diabetes in Tehranian adults. Diabetol Metab Syndr. 2020;12:87.33042230
110 Satija A, Bhupathiraju SN, Rimm EB, . Plant-Based Dietary Patterns and Incidence of Type 2 Diabetes in US Men and Women: Results from Three Prospective Cohort Studies. PLoS Med. Jun 2016;13(6):e1002039.27299701
111 Seah JYH, Ong CN, Koh WP, Yuan JM, van Dam RM. A Dietary Pattern Derived from Reduced Rank Regression and Fatty Acid Biomarkers Is Associated with Lower Risk of Type 2 Diabetes and Coronary Artery Disease in Chinese Adults. J Nutr. Nov 1 2019;149(11):2001–2010.31386157
112 Shah S, MacDonald CJ, El Fatouhi D, . The associations of the Palaeolithic diet alone and in combination with lifestyle factors with type 2 diabetes and hypertension risks in women in the E3N prospective cohort. Eur J Nutr. Oct 2021;60(7):3935–3945. doi:10.1007/s00394-021-02565-5 33909140
113 Shan Z, Li Y, Zong G, . Rotating night shift work and adherence to unhealthy lifestyle in predicting risk of type 2 diabetes: results from two large US cohorts of female nurses. Bmj. Nov 21 2018;363:k4641.30464025
114 Song S, Lee JE. Dietary Patterns Related to Triglyceride and High-Density Lipoprotein Cholesterol and the Incidence of Type 2 Diabetes in Korean Men and Women. Nutrients. Dec 20 2018;11(1)doi:10.3390/nu11010008
115 Song Z, Yang R, Wang W, . Association of healthy lifestyle including a healthy sleep pattern with incident type 2 diabetes mellitus among individuals with hypertension. Cardiovasc Diabetol. Dec 18 2021;20(1):239. doi:10.1186/s12933-021-01434-z 34922553
116 Srour B, Fezeu LK, Kesse-Guyot E, . Ultraprocessed Food Consumption and Risk of Type 2 Diabetes Among Participants of the NutriNet-Sante Prospective Cohort. JAMA Intern Med. Feb 1 2020;180(2):283–291.31841598
117 Tait CA, L’Abbe MR, Smith PM, Watson T, Kornas K, Rosella LC. Adherence to Predefined Dietary Patterns and Risk of Developing Type 2 Diabetes in the Canadian Adult Population. Can J Diabetes. Mar 2020;44(2):175–183 e2.31420278
118 Tertsunen HM, Hantunen S, Tuomainen TP, Virtanen JK. Adherence to a healthy Nordic diet and risk of type 2 diabetes among men: the Kuopio Ischaemic Heart Disease Risk Factor Study. European Journal of Nutrition. Oct 2021;60(7):3927–3934. doi:10.1007/s00394-021-02569-1 33904995
119 Teymoori F, Farhadnejad H, Mokhtari E, . Dietary and lifestyle inflammatory scores and risk of incident diabetes: a prospective cohort among participants of Tehran lipid and glucose study. BMC Public Health. Jul 2 2021;21(1):1293.34215245
120 Teymoori F, Jahromi MK, Ahmadirad H, . The association of dietary and lifestyle indices for insulin resistance with the risk of cardiometabolic diseases among Iranian adults. Sci Rep. Apr 17 2023;13(1):6224. doi:10.1038/s41598-023-33505-4 37069259
121 Tison SE, Shikany JM, Long DL, . Differences in the Association of Select Dietary Measures With Risk of Incident Type 2 Diabetes. Diabetes Care. Nov 1 2022;45(11):2602–2610. doi:10.2337/dc22-0217 36125972
122 Ushula TW, Mamun A, Darssan D, . Dietary patterns and the risks of metabolic syndrome and insulin resistance among young adults: Evidence from a longitudinal study. Clinical Nutrition. Jul 2022;41(7):1523–1531. doi:10.1016/j.clnu.2022.05.006 35667268
123 Vinke PC, Navis G, Kromhout D, Corpeleijn E. Socio-economic disparities in the association of diet quality and type 2 diabetes incidence in the Dutch Lifelines cohort. EClinicalMedicine. Feb 2020;19:100252.32140670
124 Voortman T, Kiefte-de Jong JC, Ikram MA, . Adherence to the 2015 Dutch dietary guidelines and risk of non-communicable diseases and mortality in the Rotterdam Study. Eur J Epidemiol. Nov 2017;32(11):993–1005.28825166
125 Walsh EI, Jacka FN, Butterworth P, Anstey KJ, Cherbuin N. Midlife susceptibility to the effects of poor diet on diabetes risk. Eur J Clin Nutr. Jan 2021;75(1):85–90.32651462
126 Wang F, Baden MY, Guasch-Ferre M, . Plasma metabolite profiles related to plant-based diets and the risk of type 2 diabetes. Diabetologia. Jul 2022;65(7):1119–1132. doi:10.1007/s00125-022-05692-8 35391539
127 Wang P, Song M, Eliassen AH, . Optimal dietary patterns for prevention of chronic disease. 2023;
128 Wang Y, Xu L, Wang N, . Associations of Dietary Patterns and Incident Type 2 Diabetes in a Community Population Cohort From Southwest China. Front Public Health. 2022;10:773172. doi:10.3389/fpubh.2022.773172 35186834
129 Xu Z, Steffen LM, Selvin E, Rebholz CM. Diet quality, change in diet quality and risk of incident CVD and diabetes. Public Health Nutr. Feb 2020;23(2):329–338.31511110
130 Xu CJ, Cao Z, Yang HX, Hou YB, Wang XH, Wang YG. Association Between the EAT-Lancet Diet Pattern and Risk of Type 2 Diabetes: A Prospective Cohort Study. Front Nutr. Jan 14 2022;8doi:ARTN 784018 10.3389/fnut.2021.784018
131 Yu EY, Ren Z, Mehrkanoon S, . Plasma metabolomic profiling of dietary patterns associated with glucose metabolism status: The Maastricht Study. BMC Med. Nov 21 2022;20(1):450. doi:10.1186/s12916-022-02653-1 36414942
132 Zhang S, Stubbendorff A, Olsson K, . Adherence to the EAT-Lancet diet, genetic susceptibility, and risk of type 2 diabetes in Swedish adults. Metabolism. Apr 2023;141:155401. doi:10.1016/j.metabol.2023.155401 36682448
133 Zhuang P, Liu X, Li Y, . Effect of Diet Quality and Genetic Predisposition on Hemoglobin A1c and Type 2 Diabetes Risk: Gene-Diet Interaction Analysis of 357,419 Individuals. Article in Press. Diabetes care. 2021;doi:10.2337/dc21-1051