# Summary of conclusion statements and grades

The 2025 Dietary Guidelines Advisory Committee answered the systematic review question, “What is the relationship between dietary patterns consumed and risk of type 2 diabetes?”, with the following updates to existing conclusion statements (Appendix 2: Conclusion statements from the existing systematic reviews). The grades reflect the strength of the evidence underlying the conclusion statements.^*^

* A conclusion statement is carefully constructed, based on the evidence reviewed, to answer the systematic review question. A conclusion statement does not draw implications and should not be interpreted as dietary guidance.

### Children and Adolescents

- A conclusion statement cannot be drawn about the relationship between dietary patterns consumed by children and adolescents and risk of type 2 diabetes because of substantial concerns with directness. (Grade Not Assignable)

### Adults and Older Adults

- Dietary patterns consumed by adults and older adults that are characterized by higher intakes of vegetables, fruits, legumes, nuts, whole grains, and fish/seafood and lower intakes of red and processed meats, high-fat dairy products, refined grains, and sugar-sweetened foods and beverages are associated with lower risk of type 2 diabetes. This conclusion statement is based on evidence graded as strong.

## Research recommendations

- Examine the risk for type 2 diabetes in children and adolescents using outcomes with clinically meaningful cut points indicative of prediabetes, which include fasting glucose values of 100-125 mg/dL, an HbA1c value of 5.7% to 6.4% or a 2-hour post-load glucose level of 140 to 199 mg/dL. Incident prediabetes is prevalent among U.S. children and adolescents and may be associated with a risk of progression to type 2 diabetes.
- Examine dietary patterns consumed earlier in childhood (from birth) and through adolescence in relation to changes in risk of and risk factors for type 2 diabetes, particularly HbA1C using longer term cohort or case-control studies across a range of ages and life stages.
  - Conduct trials, particularly with diverse populations in the United States, that are well-controlled for diet quality and examine to examine the effect of dietary patterns on risk factors for type 2 diabetes, particularly HbA1C.
  - Conduct systems-level approaches that examine dietary patterns, particularly among children and adolescents, and changes in outcomes to better understand other contextual and environmental factors impacting these relationships synergistically.
- Use repeat measures of dietary patterns with validated dietary assessment tools and methods at multiple times during follow-up and with more detailed descriptions of the food components consumed and preparation methods of foods as part of the dietary pattern while consistently incorporating diet quality.
- Control for confounding factors, such as family history of diabetes, that may impact the relationship between dietary patterns and risk of type 2 diabetes.
- Account for potential effect modification or mediating factors, including social determinants of health such as food insecurity status and socioeconomic position of participants.
- Include diverse populations with varying race and/or ethnicity and/or socioeconomic background.
- Collect detailed lifestyle information, especially physical activity, particularly in observational studies.