# Results

## Literature search and screening results

The articles included in this systematic review were identified from two literature searches (Appendix 4). The first literature search was conducted as part of existing systematic reviews^†^ that examined dietary patterns and risk of cardiovascular disease, growth, body composition, and risk of obesity, as well as risk of type 2 diabetes outcome in a combined way. NESR analysts identified 28 articles from that literature search that examined dietary patterns and risk of type 2 diabetes that met inclusion criteria for this systematic review update and were not also included in the second literature search. The second literature search was conducted to identify articles specifically on dietary patterns and risk of type 2 diabetes since the first literature search was conducted. The results of the second literature search yielded 13,478 records after the removal of duplicates (see Figure 2). Dual-screening resulted in the exclusion of 11,336 titles, 1,384 abstracts, and 653 full-texts articles. Reasons for full-text exclusion are in Appendix 5: Excluded articles. The body of evidence includes 133 articles published since October 2019 in children and adolescents (n=15), or since January 2014 in adults and older adults (n=118). In addition, this review updates graded conclusion statements from existing reviews that were based on 1 article in children and adolescents^†^ and 37 articles in adults and older adults.^*^ No articles met inclusion that examined infants and young children up to age 24 months, individuals during pregnancy, or individuals during postpartum.

† Boushey C, Ard J, Bazzano L, . Dietary Patterns and Risk of Type 2 Diabetes: A Systematic Review. July 2020. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. https://doi.org/10.52570/NESR.DGAC2020.SR0103

* Dietary Patterns Technical Expert Collaborative and NESR Staff. A Series of Systematic Reviews on the Relationship Between Dietary Patterns and Health Outcomes. March 2014. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://nesr.usda.gov/sites/default/files/2019-06/DietaryPatternsReport-FullFinal2.pdf

Figure 2 Literature search and screening flow chart.

The literature search in PubMed, Embase, Cochrane, and CINAHL, retrieved 13,478 records after removing duplicates. 28 were included from existing reviews. 0 were found with manual search methods. 11,336 titles, 1,384 abstracts, and 653 full-texts were excluded. 133 articles were included in the systematic review.

## Children and adolescents

The 2025 Dietary Guidelines Advisory Committee updates the existing systematic review by synthesizing an additional 15 articles that were published since October 2019, met inclusion criteria, and assessed how this new evidence relates to the conclusion statement from the existing systematic review.^1–15^ The 15 articles examined the relationship between dietary patterns consumed by children and adolescents and risk of type 2 diabetes using the following study designs: 1 randomized controlled trial^1^ and 14 prospective cohort studies.^2–15^

### Description of the evidence

#### Population

Sample sizes ranged from N=70 to N=3991 participants. Studies enrolled participants regardless of risk for chronic disease or sex, except one intervention that exclusively enrolled female adolescents defined as meeting criteria for the metabolic syndrome.^1^ The mean duration of follow-up time ranged from 12 weeks in the intervention to ~31 years (at age ~42 years) in observational studies.

Regarding the socioeconomic position (SEP) of participants, 7 articles reported parent/maternal education^4,7,9,10,12,14,15^ and 2 reported household income.^2,13^ None of the articles reported the specific distribution of participants by race and/or ethnicity, but many indicated heritage and/or birth country of participants, (e.g., 67.4% Dutch). Multiple articles from a single cohort study were included, but each article reported results for distinct dietary patterns and/or outcomes. Studies were conducted in the following countries: Australia; Finland; Germany; Iran; Ireland; Mexico; The Netherlands; Portugal; United Kingdom; and multiple countries (Germany, Belgium, Italy, Poland, and Spain).

#### Intervention/exposure and comparator

Dietary patterns during childhood or adolescence were assessed in participants at ages ranging from 2 up to 21 years. The most common dietary intake assessment method was food frequency questionnaire,^2,3,6–9,12,13,15^ and other methods were diet records, histories, or food diaries.^4,5,10,11,14^ Repeat measures of diet assessments were conducted in 5 articles^4,5,7,11,15^ while the remaining analyzed dietary pattern exposure status at study baseline only. Methods used to examine dietary patterns included:

- Investigator-assigned dietary intervention^1^
- A priori index or score derivation^2–4,6,9,11,13,14^
- Factor, cluster, or latent class analysis^5,7,10,12,15^

Labels or names of dietary patterns varied across studies and included many “Mediterranean” style indices that differed between and within studies, several scores aligned with a Dietary Approaches to Stop Hypertension (DASH) diet, as well as investigator-defined names such as “Core Foods” or “Traditional”, which do not clearly indicate the composition of the dietary patterns compared.

#### Outcome

All but one of the studies collected fasted blood samples clinically using standard methods. One article reported collecting non-fasted blood to assess lipid status as well as insulin. None of the included articles reported outcomes of type 2 diabetes or prediabetes incidence. The following outcomes were reported in the included studies:

- Fasting blood glucose^1–15^
- Insulin and/or Insulin Resistance (e.g., Homeostatic Model Assessment for Insulin Resistance, HOMA-IR)^1,2,4,6–8,10–13^

Articles examined these measures continuously, 3 articles examined them categorically with high risk cut-points that defined as elevated fasting blood glucose ≥100 mg/dL^3,5,15^ and 1 article defined it as HOMA-IR, insulin, or fasting blood glucose ≥ 80th percentile.^4^

### Synthesis of the evidence

Results across the body of evidence suggest that dietary patterns assessed among children and adolescents that reflect higher or high intakes of vegetables, fruit, nuts and legumes, grains (particularly whole grains), fish/seafood, and lower or low intakes of red and processed meat and sugar-sweetened foods and beverages may be related to lower HOMA-IR, insulin, and/or blood glucose. Support for this association is evident by 9 of the 16 articles that are described further below. However, the reported magnitude of effect estimates, variance around effect estimates, and statistical significance varied across the evidence. Incident diagnosis of type 2 diabetes, as a primary outcome of interest, was not examined in any of the included studies.

○ One intervention^1^ found that adolescents at mean age 13 to 18 years, who were randomized to consume a dietary pattern higher in vegetables, fruits, grains and lower in meat and meat products and sugar compared to a control group consuming their usual diet, had lower mean HOMA-IR, fasting blood glucose, and fasting insulin after 12 weeks. The trial was conducted in Iran among only female participants with metabolic syndrome and the intervention group reported consuming diets higher in total fat, MUFA, and fiber than the control group at the end of follow-up
○ Two articles^2,3^ observed that adolescents at mean ages 13.6 to 16.4 years with higher (vs. lower adherence) scores for a dietary pattern reflecting higher intakes of vegetables, fruit, nuts and legumes, whole grains, fish/seafood, low-fat dairy, and lower in red and processed meat, sweetened beverages and sodium had statistically lower risk of elevated fasting glucose^3^ and lower mean fasting insulin levels at follow-up.^2^
○ Buckland and colleagues^4^ reported that adolescents at mean age 13 years with higher (vs. lower adherence) scores for a dietary pattern reflecting higher in vegetables, fruit, pulses, legumes, grains and grain products, fish and seafood, dairy products, ratio of PUFA+MUFA/SFA, and lower in meat and meat products had statistically lower fasting insulin and HOMA-IR at ages 17 and 24 years, but fasting glucose did not differ.
○ Chan She Ping-Delfos and colleagues^6^ found that adolescents at age 14 years with higher (vs. lower adherence) scores for a dietary pattern reflecting higher intakes of vegetables and legumes, fruit and 100% fruit juice, grains and whole grains (relative to total), unprocessed meat and alternatives, low and reduced-fat dairy products, water as a beverage, ‘healthy’ fats, and low in ‘extra’ foods) had statistically lower mean fasting insulin and HOMA-IR levels at age 17 years, but fasting glucose levels did not differ.
○ Pinto and colleagues^12^ observed that two dietary patterns at age 7 years (derived using different methods but similarly reflecting higher intakes of processed meat and other energy-dense foods such as pizza, French fries and sugar-sweetened foods and beverages and lower or low in vegetables and/or fish) were associated with statistically higher HOMA-IR values ~ 3 years later, but not fasting blood glucose.
○ Wu and colleagues^15^ reported that children at age 9 years with a dietary pattern trajectory that shifted towards higher intakes of pork, other meats, sausages, eggs, fish, potatoes, alcoholic beverages and lower intakes of tea was related to statistically higher risk of impaired glucose by age ~ 30 years.
○ Bull and Northstone (2016)^5^ observed that children at age 10 years with a dietary pattern comprised of processed meat, pies and pasties, coated and fried chicken and white fish, pizza, chips, baked beans and tinned pasta, chocolate, sweets, sugar, diet and regular fizzy drinks had statistically higher risk of elevated fasting glucose at age 17 years. Consumption of this dietary pattern at ages 7 or 13 years was not associated with outcomes at follow-up.

### Conclusion statement and grade

The 2025 Dietary Guidelines Advisory Committee updated the existing systematic review but did not develop a conclusion statement^*^ about the relationship between dietary patterns consumed by children and adolescents and risk of type 2 diabetes due to substantial concerns with directness of the evidence.

* A conclusion statement is carefully constructed, based on the evidence reviewed, to answer the systematic review question. A conclusion statement does not draw implications and should not be interpreted as dietary guidance.

Table 5 Conclusion statement, grade for dietary patterns consumed by children and adolescents and risk of type 2 diabetes

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between dietary patterns consumed by children and adolescents and risk of type 2 diabetes because of substantial concerns with directness.
Grade | Grade Not Assignable
Body of Evidence | 15 articles (1 RCT; 14 prospective cohort studies) assessed as they relate to the evidence in the existing review (1 article)
Rationale | - Substantial concerns with directness given no studies examined the primary outcome of incident diagnosis of type 2 diabetes; - Serious concerns due to variation in the magnitude of effect estimates, lack of statistical significance and/or wide confidence intervals.; - Some concerns with risk of bias for potential confounding, including family history of diabetes and potential for exposure measurement error.

The body of evidence includes 15 articles published since 2019, assessed as they relate to the evidence included in the existing review^†^ and examined dietary patterns consumed by children and adolescents and risk of type 2 diabetes. Dietary patterns were investigated using a variety of study designs and analytic methods including a randomized dietary intervention, index/score analysis, factor/cluster analysis and latent class analysis. Outcome measures included only intermediate measures for type 2 diabetes, such as fasting blood glucose, insulin, and/or HOMA-IR, with no studies examining type 2 diabetes incidence. This review did not examine clinically prescribed diets for the purposes of treating or managing diagnosed type 2 diabetes. While some evidence suggested that improved type 2 diabetes risk factors may be related to the consumption of dietary patterns with higher or high intakes of vegetables, fruit, nuts and legumes, grains (particularly whole grains), fish/seafood, and lower or low intakes of red and processed meat and sugar-sweetened foods and beverages in children and adolescents, there were substantial limitations described further below.

† Boushey C, Ard J, Bazzano L,. Dietary Patterns and Risk of Type 2 Diabetes: A Systematic Review. July 2020. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://doi.org/10.52570/NESR.DGAC2020.SR0101

A conclusion could not be drawn because of substantial concerns with directness due to a lack of studies examining the clinical outcome of type 2 diabetes risk. Endpoints included outcomes of intermediate risk (e.g., elevated fasting glucose), which may be due to the relatively low risk of diabetes incidence in children and adolescence for prospective cohort studies, and the short-term intervention period for the dietary intervention trial. Evidence included studies examining eligible biochemical markers of diabetes risk, such as fasting blood glucose, insulin, and HOMA-IR. Most of these studies reported blood glucose measurements on a continuous scale, with few using clinical cut points for elevated fasting glucose, HbA1c, or prediabetes, posing a challenge to drawing conclusions for dietary patterns and prevention of clinical outcomes. Although a grade could not be assigned, limitations were identified across the body of evidence. There was variation across the evidence in the direction and magnitude of effects, with many of the studies reporting no associations between dietary patterns and the outcomes. Sample sizes were relatively large to indicate sufficient power for continuous trait outcomes. Studies were at higher risk of bias across multiple domains (Table 8), which may have biased their results. Most of the studies were at a high risk of bias from confounding, especially from family history of diabetes which may serve as a proxy of both genetic risk and shared home environment/lifestyle) and race and/or ethnicity of participants. Many studies also had high risk of bias due to potential exposure measurement error, given they analyzed diet collected at baseline only and did not account for changes in diet over time or they used diet assessment tools with uncertain validity in their study population. All of the studies directly examined the relationship between dietary patterns and diabetes-related glycemic traits that apply to the U.S. population, such as fasting blood glucose, insulin, and HOMA-IR. However, none of the studies explicitly included follow-up and analysis of incident clinical type 2 diabetes diagnosis. None of the studies were conducted in the U.S. but examined dietary patterns that would likely apply to the U.S. population with a few exceptions (e.g., “Traditional Finnish”). This body of evidence includes both large and small studies (with statistically significant as well as null findings) so publication bias may be less likely.

Table 6 Evidence examining the relationship between dietary patterns consumed by children and adolescents and risk of type 2 diabetes^*^ * Abbreviations: BMI, Body mass index CVD, Cardiovascular disease; EDF, Energy-dense food; FBG, fasting blood glucose; FBI, fasting blood insulin; FFQ, Food frequency questionnaire; FPG, fasting plasma glucose; F/U, Follow-up; HbA1C, Hemoglobin A1C; HDL-C, high-density lipoprotein cholesterol; HOMA-IR, Homeostatic Model Assessment for Insulin Resistance; IFG, impaired fasting glucose; LFU, lost to follow-up; mo, months; MUFA, monounsaturated fatty acid; NFG, normal fasting glucose; NR, not reported; NS, not statistically significant; OGTT, oral glucose tolerance test; OR, odds ratio; PUFA, polyunsaturated fatty acid; Q, quantile; SFA, saturated fatty acid; SEP/SES, Socioeconomic position/status; SS, regression coefficient; T, tertile; T1D, Type 1 Diabetes Mellitus; T2D, Type 2 Diabetes Mellitus; TEI, total energy intake; WC, waist circumference; UK, United Kingdom; UPF, Ultra-processed food; US, United States; y, years; ♂ male; ♀ female; ∆ change or delta

Article Information | Intervention/exposure and comparator | Results | Methodological considerations
Asodeh, 2023^1^; Iran, [underlined: RCT]; Analytic N=70; Selection data: Enrolled only female adolescents with metabolic syndrome who were not on a specific diet in the past 3 months | Age at dietary pattern: 14y, mean; 13 to 18y; [underlined: Mediterranean diet]: Consumed similar vegetables, fruits, grains, meat and meat products, sugar, but significantly higher total fat, MUFA, and fiber than [underlined: Control group,] which was assigned to usual dietary recommendations (consumed significantly less total fat, MUFA, and fiber than Mediterranean group); Method: Investigator-assigned dietary intervention | F/U: 12 weeks; - FBG, mean ± SE: 0.6 ±0.9 v. −5.6 ±0.9; p<0.001; - FBI, mean ± SE: −1.8 ±0.7 v. −4 ±0.7; p=0.04; - HOMA-IR, mean ± SE: −0.35 ±0.1 v. −1.07 ±0.1; p<0.01; Summary: Inverse: Meditteranean diet v. Control & FBG, HOMA-IR after 12 weeks; Inverse, NS: FBI after 12 weeks | - Intensity was relatively high: control group was only given verbal instruction; - Diet adherence via 3-day diet records; - Fasted (10-12 hour) blood samples collected; HOMA-IR calculated as FPG (mmol/l) x FBI (mU/l)/22.5; - Funding: Tehran Endocrine and Metabolism Research Center and the Tehran University of Medical Science
Aljahdali, 2022^2^; Mexico; Early Life; Exposure in Mexico to Environmental Toxicants (ELEMENT); Analytic N=574; Selection data: Enrolled pregnant mothers from low-middle income prenatal clinics; Included those who attended at least one of three follow-up visits; had data for at least one of eight cardiometabolic risk factors (waist circumference, Blood pressure, FBG, fasting triglycerides, fasting HDL-C, fasting insulin, and HOMA-IR); had dietary information | Age at dietary pattern: 8 to 14 y, mean 10.3; 10 to 18 y, mean 14.5y; 12 to 21 y, mean 16.4; [underlined: Alternate Med Diet Score (aMED)] [Fung 2005] Positive: Vegetables; (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA/SFA. Negative: Red and Processed Meat. Neutral: Alcohol; [underlined: DASH score] [Fung 2008]: Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Sodium; Method: Index/score | Age at outcome: 12 to 21 y, mean 16.4; DASH score & FBG; - Q2, β: −0.01824 (0.01016); p-trend= 0.0730; - Q3, β: −0.00317 (0.01002); p-trend=0.7520; - Q4, β: −0.02130 (0.01076); p-trend=0.0481; - Continuous, β: −0.00144 (0.001019); p-trend=0.1571; aMED & FBG; - Q2, β: −0.00098 (0.01132); p-trend=0.9310; - Q3, β: −0.00785 (0.01002); p-trend= 0.4331; - Q4, β: 0.007172 (0.01254); p-trend=0.5674; - Continuous, β: −0.00025 (0.002693); p-trend=0.9251; DASH score & Fasting Insulin; - Q2, β: −0.1192 (0.05586); p-trend=0.0332; - Q3, β: −0.05021 (0.05519); p-trend=0.3633; - Q4, β: −0.1943 (0.06607); p-trend=0.0034; - Continuous, β: −0.01475 (0.006133); p-trend=0.0164; DASH score & HOMA-IR; - Q2, β: −0.1502 (0.06118); p-trend=0.0143; - Q3, β: −0.06758 (0.05980); p-trend=0.2588; - Q4, β: −0.2482 (0.07341); p-trend=0.0008; - Continuous, β: −0.01893 (0.006733;p-trend=0.0050; aMED & Fasting Insulin; - Q2, β: −0.01011 (0.06014); p-trend=0.8666; - Q3, β: −0.03920 (0.05608); p-trend= 0.4847; - Q4, β: −0.06270 (0.07777); p-trend=0.4204; - Continuous, β: −0.01457 (0.01600); p-trend=0.3628; aMED & HOMA-IR; - Q2, β: −0.01370 (0.06598); p-trend=0.8356; - Q3, β: −0.05244 (0.06160); p-trend= 0.3948; - Q4, β: −0.03106 (0.08427); p-trend=0.7126; - Continuous, β: −0.01332 (0.01759); p-trend=0.4491; Summary:; - Inverse: DASH (categorical) & Insulin (NS, Glucose; Null: DASH (continuous) & Insulin; Glucose; - Null: aMED & Glucose, Insulin | - Did not account for: Race and/or Ethnicity (100% Mexican-heritage, birth cohort); Anthropometry at baseline was not accounted for in T2D results; - FFQ was not formally validated; Unclear methods used to derive single estimate from multiple times; Time points used in analyses are unclear;; - Fasted blood samples collected; HOMA-IR calculated; - Post-exposure intervention of maternal Ca+ supplementation trial in subset; Results not be generalizable to those not from Mexico City; - Funding: US Environmental Protection Agency; National Institute for Environmental Health Sciences; National Institute of Public Health/Ministry of Health of Mexico
Asghari, 2016^3^; Iran; Tehran Lipid and Glucose Study; Analytic N=424; Selection data: Excluded those with incomplete/missing diet or outcome data; with Metabolic Syndrome, Hypertension, High triglycerids, blood pressure or fasting plasma glucose, Low HDL-C, or Abdominal obesity at baseline | Age at dietary pattern: 13.6 y, mean; 6 to 18 y; [underlined: DASH score] [Fung, 2008]: Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Q4 v. Q1 ref had higher vegetables (2.1x), fruits (2.4x), nuts, legumes, and seeds (1.5x), whole grains (1.5x), low fat dairy (0.6x), lower red and processed meat (0.5x), sweetened beverages (1.6x), and sodium (0.3x); Method: Index/score | Age at outcome: ~17 y (3 y follow-up); DASH score & FPG; - Q2, OR: 1.05, 95% CI: 0.50, 2.23; - Q3, OR: 0.68, 95% CI: 0.30, 1.55; - Q4, OR: 0.40, 95% CI: 0.15, 0.99; - p-trend=0.038; Summary: Inverse: DASH (Q4 v. Q1 ref) & odds of high-FPG | - Did not account for: Race/ethnicity (Iranian), SEP; - Diet assessed using a validated 168-item FFQ at baseline only; - Fasted (14-hour) blood samples collected; “High” FPG was based on ≥ 100 mg/dL or drug treatment; - Funding: National Research Council of the Islamic Republic of Iran and the Research Institute for Endocrine Sciences, Shahid Beheshti University of Medical Sciences
Buckland, 2022^4^; United Kingdom; Avon Longitudinal Study of Parents and Children (ALSPAC); Analytic N=1940 17y; 1961 24y; Selection data: Excluded those diagnosed with diabetes, on insulin therapy, or FBG ≥ 7 mmol/L; extreme outliers on cardiometabolic score components; those with incomplete dietary data | Age at dietary pattern: 7 y; [underlined: Children’s relative Mediterranean-style] [underlined: diet score] (C-rMED) [Buckland, 2022]: Positive: Fruit (including nuts and seeds), vegetables (excluding potatoes), pulses, cereals and cereal products, dairy products, legumes, fish and seafood, MUFA+PUFA/SFA. >Negative: meat and meat products; Method: Index/score | Age at outcome: 17y, 24y:; FBG at age 17y; - c-r-Med 7y: OR: 1.04, 95% CI: 0.94, 1.15; - c-r-Med 10y: OR: 1.11, 95% CI: 1.01, 1.23; - c-r-Med 13y: OR: 1.02, 95% CI: 0.92, 1.13; FBG at age 24y; - c-r-Med 7y: OR: 1.06, 95% CI: 0.96, 1.17; - c-r-Med 10y: OR: 1.04, 95% CI: 0.94, 1.15; - c-r-Med 13y: OR: 0.94, 95% CI: 0.85, 1.04; Insulin at age 17 y; - c-r-Med 7y: OR: 0.99, 95% CI: 0.90, 1.09; - c-r-Med 10y: OR: 1.01, 95% CI: 0.92, 1.12; - c-r-Med 13y: OR: 0.87, 95% CI: 0.79, 0.97; Insulin at age 24y; - c-r-Med 7y: OR: 1.00, 95% CI: 0.90, 1.10; - c-r-Med 10y: OR: 0.95, 95% CI: 0.86, 1.05; - c-r-Med 13y: OR: 0.84, 95% CI: 0.76, 0.93; HOMA-IR at age 17y; - c-r-Med 7y: OR: 1.00, 95% CI: 0.91, 1.11; - c-r-Med 10y: OR: 1.00, 95% CI: 0.90, 1.10; - c-r-Med 13y: OR: 0.88, 95% CI: 0.79, 0.97; HOMA-IR at age 24y; - c-r-Med 7y: OR: 0.99, 95% CI: 0.89, 1.09; - c-r-Med 10y: OR: 0.94, 95% CI: 0.85, 1.04; - c-r-Med 13y: OR: 0.88, 95% CI: 0.80, 0.97; Summary: Inverse: C-rMED at 13y & insulin and HOMA-IR at ages 17 and 24y; Positive: C-rMED at 13y & FBG at age 24y | - Did not account for: Anthropometry at baseline, Race/Ethnicity; - Dietary intake from 3-day diet diary at 7y (parent), 10 and 13y (parent with child); C-rMED from only age 7y data; - Fasted (8-10 hour) blood samples collected; HOMA-IR calculated as FPG mg/dL x FBI mU/L/405; - Funding: UK Medical Research Council and Wellcome, University of Bristol, Wellcome Trust and MRC, The British Heart Foundation, British Heart Foundation Research Fellowship, MRC Career Development Award
Bull and Northstone, 2016^5^; United Kingdom; Avon Longitudinal Study of Parents and Children (ALSPAC); Analytic N=2311; Selection data: Excluded those with missing data on cardiovascular measures, dietary patterns info at all time points, and covariable data | Age at dietary pattern: 7, 10, and 13y; “[underlined: Healthy]”, ref: Non-white bread, reduced-fat milk, cheese, yoghurt and fromage frais, butter, breakfast cereal, rice, pasta, eggs, fish, vegetable and vegetarian dishes, soup, salad, legumes, fruit, crackers and crispbreads, high-energy-density sauces (e.g. mayonnaise), fruit juice, water; [underlined: “Processed”:] Processed meat, pies and pasties, coated and fried chicken and white fish, pizza, chips, baked beans and tinned pasta, chocolate, sweets, sugar, diet and regular fizzy drinks; [underlined: “Traditional]”: Red meat, poultry, potatoes, vegetables, starch-based products, low-energy-density sauces, puddings, tea, coffee; “[underlined: Packed Lunch]”: White bread, margarine, ham and bacon, sweet spreads, salty flavourings, crisps, biscuits, diet squash, tea, coffee; Method: Factor/cluster analysis | Age at outcome: 17y; Dietary patterns at age 7y and high FBG; - ‘Healthy’, OR: 1.61, 95 % CI: 0.96, 2.69; p=0.07; - ‘Processed’, OR: 1.2, 95 % CI: 0.71, 2.04; p=0.5; - ‘Traditional’, OR: 1.17, 95 % CI: 0.66, 2.08; p=0.59; Dietary patterns at age 10y and high FBG; - ‘Processed’, OR: 0.47, 95 % CI: 0.27, 0.83; p=0.01; - ‘Traditional’, OR: 0.74, 95 % CI: 0.45, 1.22; p=0.24; - ‘Packed-lunch’, OR: 0.67, 95 % CI: 0.39, 1.17; p=0.16; Dietary patterns at age 13y and high FBG; - ‘Healthy’, OR: 0.71, 95 % CI: 0.44, 1.16; p=0.17; - ‘Processed’, OR: 0.84, 95 % CI: 0.50, 1.4; p=0.5; - ‘Traditional’, OR: 0.7, 95 % CI: 0.39, 1.26; p=0.23; Summary: ‘Processed’ v. ‘Healthy’ at age 10y & High FBG; Null: all other dietary patterns and high FBG | - Did not account for: Anthropometry (adjusted for birth weight, gestational age), Race/ethnicity, Physical activity; - Diet assessed with 3-day diary once each age time point; Unclear if diet assessment methods were valid/reliable; Serious concerns with accuracy of data tables; - Fasted (6-hour) blood samples collected; - Funding: The United Kingdom Medical Research Council; Wellcome Trust; University of Bristol
Chan She Ping-Delfos, 2015^6^; Australia; Western; Australian Pregnancy Cohort; Analytic N=1419; Selection data: Excluded those with missing data, implausible energy intake | Age at dietary pattern: 14 y; [underlined: Dietary Guideline Index for Children] [underlined: and Adolescents (DGI-CA]): Fruit/100% fruit juice, vegetables and legumes, breads and cereals, wholegrain bread relative to total, meat and alternatives (excluding processed meat); dairy products: reduced- or low-fat dairy, water as a beverage, healthy fats: total fats, <3/d ‘extra foods’; Method: Index/score | Age at outcome: 17y; - FBG, β: −0.001, 95 % CI: −0.003,0.001; p=0.404; - FBI, β: −0.028, 95 % CI: −0.042,-0.006; p=0.01; - HOMA-IR, β: −0.004, 95 % CI: −0.007,-0.001; p=0.005; Summary:; Inverse: DGI-CA score & HOMA-IR, FBI Null: DGI-CA score & FBG | - Did not account for: Race/ethnicity; - Diet assessed once at baseline with record validated in adults only; - Fasted blood samples collected; HOMA-IR calculated; - Funding: University of Western Australia; the Faculty of Medicine, Dentistry and Health Sciences at the University of Western Australia; the Telethon Kids Institute; the Women and Infants Research Foundation; Curtin University; and the Raine Medical Research Found
Costa, 2023^7^; Portugal; Epidemiological Health Investigation of Teenagers in Porto (EPITeen); Analytic N=862; Selection data: Excluded those with missing or outliers of dietary/outcome data | Age at dietary pattern: 13y; [underlined: ‘Lower intake’]: lower consumption of majority food groups; ‘[underlined: Healthier’]: highest consumption of seafood, soup, vegetables/legumes, fruit, and added fats; [underlined: ‘Dairy products’]: highest consumption of dairies; [underlined: ‘Fast food and sweets’]: fast food, sweets and pastry, soft drinks and coffee or tea; Method: Factor or cluster analysis | Age at outcome: 21y; mean FBG, mg/dL; - ‘Lower intake’, 84, 95% CI: 82, 85; - ‘Healthier’, 83, 95% CI: 82, 85; - ‘Dairy products’, 83, 95% CI: 82, 85; - ‘Fast food and sweets’, 84, 95% CI: 82, 86; - p=0.734; mean FBI, uUI/mL; - ‘Lower intake’, 8.94, 95% CI: 8.37, 9.5; - ‘Healthier’, 8.29, 95% CI: 7.44, 9.13; - ‘Dairy products’, 8.61, 95% CI: 7.99, 9.24; - ‘Fast food and sweets’, 9.04, 95% CI: 8.14, 9.94; - p=0.436; HOMA-IR; - ‘Lower intake’, 1.87, 95% CI: 1.74, 2; - ‘Healthier’, 1.71, 95% CI: 1.52, 1.91; - ‘Dairy products’, 1.78, 95% CI: 1.64, 1.92; - ‘Fast food and sweets’, 1.89, 95% CI: 1.68, 2.09; - p=0.436; Summary: Null: Each dietary pattern & FBG, FBI, or HOMA-IR | - Did not account for: Race and/or Ethnicity, Physical activity; - Diet assessed at multiple time points (age 13y, 21y) using a FFQ validated in adults; No differences between those included or excluded due to LFU; Data on dietary patterns foods/food groups reported in Araujo, 2015 doi: 10.1016/j.nut.2014.06.007; - Fasted blood samples collected at age 13y and 17y; - Funding: Portuguese Foundation for Science and Technology; University of Porto
Durão, 2022^8^; Portugal; Generation XXI; Analytic N=1861 girls; 1962 boys; Selection data: Excluded those with conditions that affect dietary intake and celiac disease, incomplete data on physical activity and screen time at 4 years, incomplete data on maternal BMI at 4 years, or no blood pressure data at 10 years. | Age at dietary pattern: 4 y; [underlined: ‘Energy-dense foods’ (EDF]): high intakes of sweets, sugar-sweetened beverages, savory pastry, and processed meat.; [underlined: ‘Snacking’:] lower in foods usually consumed at lunch and dinner (e.g., vegetables on a plate, fish, meat, rice/pasta/potatoes), higher in intermediate foods typically eaten at snacking occasions; [underlined: ‘Healthier’]: higher consumption of fruit, vegetables, vegetable soup, and fish, with a lower consumption of EDF; Method: Factor or cluster analysis | Age at outcome: 10y; FBG; - ♀ EDF, SS: 0.099, 95 % CI: −0.058, 0.256; - ♀ Snacking, SS: −0.102, 95 % CI: −0.331, 0.126; - ♂ EDF, SS: −0.11, 95 % CI: −0.274, 0.054; - ♂ Snacking, SS: −0.052, 95 % CI: −0.277, 0.173; FBI; - ♀ EDF, SS: 0.14, 95 % CI: −0.001, 0.282; - ♀ Snacking, SS: 0.111, 95 % CI: −0.094, 0.316; - ♂ EDF, SS: 0.013, 95 % CI: −0.125, 0.152; - ♂ Snacking, SS: 0.102, 95 % CI: −0.088, 0.292; HOMA-IR; - ♀ EDF, SS: 0.135, 95 % CI: −0.008, 0.278; - ♀ Snacking, SS: 0.092, 95 % CI: −0.115, 0.3; - ♂ EDF, SS: −0.006, 95 % CI: −0.146, 0.133; - ♂ Snacking SS: 0.09, 95 % CI: −0.102, 0.282; Summary: Null: Snacking, EDF & Fasting blood insulin, FBG, or HOMA-IR in girls or boys | - Did not account for: Race/Ethnicity; - Diet assessed once at baseline with FFQ validated in adults only (sub-sample verified with 3-day diary); - Fasted (8-10 hour) blood samples collected; HOMA-IR calculated; - Funding: Health Operational Programme–Saúde XXI, Community Support Framework III, Regional Department of Ministry of Health, FEDER–COMPETE, the Foundation for Science and Technology–FCT, a Researcher Contract, Epidemiology Research Unit and Laboratory for Integra
Krijger, 2021^9^; Netherlands; Amsterdam Born Children and their Development (ABCD); Analytic N=869; Selection data: Excluded those with missing data; congenital CVD; used drugs intervening with CVD factors | Age at dietary pattern: 5 to 6y; [underlined: DASH score] [Fung, 2008]: Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; [underlined: Child Diet Quality Score (CDQS)] [van der Velde, 2019]: Positive: fruits, vegetables, whole grains, fish, legumes, nuts, dairy, oils and soft liquid fats. Negative: sugar-containing beverages and processed meat; Method: Index/score | Age at outcome: 11 to 12y; DASH score & FBG; - Q1: 4.94 (0.05); - Q2: 4.88 (0.04); - Q3: 4.88 (0.05); - Q4: 4.97 (0.05); - Q5: 4.81 (0.05); - p = 0.350; CDQS & FBG; - Q1: 4.96 (0.05); - Q2: 4.89 (0.05); - Q3: 4.94 (0.05); - Q4: 4.86 (0.05); - Q5: 4.87 (0.05); - p = 0.108; Summary: Null: DASH or CDQS & FBG | - Did not account for: Race/Ethnicity (75% Dutch); - Diet assessed once at baseline with FFQ validated in children age 4-6y; - Fasted (3 hour) finger prick; - Some concerns with follow-up window and selection of reported results; - Funding: Netherlands Organization for Health Research and Development, The Dutch Heart Foundation and Sarphati Amsterdam.
Luque, 2021^10^; Germany, Belgium, Italy, Poland, and Spain; CHildhood Obesity Project (EU CHOP) trial; Analytic N=399; Selection data: Excluded those with incomplete diet /anthropometry data; moved from study region; illness or medication interfering with growth; lost contact; refusal | Age at dietary pattern: 2 y; 8y; ‘[underlined: Core Foods Pattern’]: Higher intakes of fruit, vegetables, potatoes, fish, white and red meat, and olive oil; [underlined: ‘Poor-Quality Fats and Sugars’]: Positively associated with intakes of potatoes, soft cheese, saturated spreads, fruit juices, and teas and negatively associated with intakes of fish and olive oil; [underlined: ‘Protein Sources’]: Vegetables, potatoes, white meat, red meat, processed fish, eggs, chips and snacks, flavored milk; Method: Factor or cluster analysis | Age at outcome: 8y; HOMA-IR; - ‘Core’: β: −0.02, 95% CI: −0.05, 0.00; p=0.043; - ‘Protein’: β: 0.01, 95% CI: −0.02, 0.04; p=0.412; - ‘Fats and Sugars’: β: −0.00, 95% CI: −0.03, 0.03; p=0.916; SEM, direct effects; - ‘Core’ : β: −3.91, p=0.034; - ‘Protein’: β: 0.21, p<0.001; Summary: Inverse: ‘Core’ & HOMA-IR; Null: ‘Fats and Sugars’ & HOMA-IR; Positive: ‘Protein’ & HOMA-IR | - Did not account for: Race/Ethnicity, Physical activity; - Diet assessed at age 2y and 8y with 3-day weighted food diaries; Correlated intakes between 2y & 8y; - Fasted blood samples collected using ‘routine methods’; - Funding: 5th-7th Framework Program, European Union’s Horizon 2020 research and innovation programe
McCourt, 2014^11^; Ireland; Young Hearts I & III; Analytic N=487; Selection data: NR | Age at dietary pattern: 12 to 15y; [underlined: Mediterranean Diet Score (MDS)] [Trichopolou 2003]: Positive: Vegetables; Legumes; Fruit, Nuts; Cereals; Fish; MUFA/SFA. Negative: Red and Processed Meat; Dairy Products. Neutral: Alcohol; Method: Index/score | Age at outcome: 20 to 25y:; MDS & HOMA-IR, mean [SD]; - Least-least adherent: 2.6 [2.1]; - Least-most adherent: 2.6[2.1]; - Most-least adherent: 2.1[0.7]; - Most-most adherent: 1.8[0.9]; - p=0.139; Summary: Null: MDS at YH1 & HOMA at YH3 | - Did not account for: Race/Ethnicity (Irish); - Diet assessed with 7-day diet history at multiple time points; - Fasted blood samples collected (YH3) but non-fasted used (YH1); - Missingness not clearly accounted for; - Funding: YHI: Northern Ireland Chest, Heart and Stroke Association and the Department of Health and Social Services; YHIII: Wellcome Trust, British Heart Foundation.
Pinto, 2020^12^; Portugal; Generation XXI birth cohort Analytic N=3350; Selection data: Excluded twins and those without data on variables of interest (dietary data at age 7 y; cardiometabolic data at age 10 y) | Dietary pattern age(s): 7 y; [underlined: ‘PCA-1’]: Characterized by EDF (sugary drinks, sweets and salty snacks), negatively associated with Fish; Veg. soup; Fruits. Factor loadings, Positive: Ice cream; Sausage; Meat salty snacks; Fish snacks; Pizza, hamburger; French fries/chips, Cookies and biscuits; Cakes; Chocolate/snacks; Sugar; Candies; Butter or margarine; Coffee with milk; Coke; Soft drinks (Carbonated and non-carbonated); Ice Tea; Nectar juices.; [underlined: ‘PCA-2’]: Characterized by “healthier” foods; Factor loadings, Positive: Skim/Low-fat Milk; Yogurt; Cheese; Eggs; Ham (chorizo); Fish/seafood; Veg. soup; Vegetables (boiled and raw); Fruit Bread; Rice, potatoes, pasta; Crackers; Butter or margarine; Tea infusions; Natural fruit juice. Negative: Fish/seafood; Veg. soup; Fruit; ‘[underlined: PLS-1’]: Characterized by Processed meat, EDF (cakes; soft drinks), low in vegetables (veg. soup); Factor loadings, Positive: Ice cream; Cheese; Sausage; Ham (chorizo); Bread; Cakes; Coffee with milk; Coke; Soft drinks (Carbonated and non-carbonated). Negative: Whole milk; Veg. soup; ‘[underlined: PLS-2’]: Characterized by Fish; Lower intakes of EDF, Sugary drinks; Factor loadings, Positive: Fish/seafood; Negative: Chocolate milk; Ice cream; Sausage; Meat salty snacks; Fish snacks; Pizza, hamburger; Breakfast cereals; Crackers; Cookies and biscuits; Chocolate/snacks; Coke; Soft drinks (Carbonated and non-carbonated); Iced Tea; Nectar juices.; [underlined: “EDF”:] Characterized by Sweets, soft drinks, salty pastry, processed meat; [underlined: “Snacking]”: Characterized by Snack foods, lower in fish, meat, eggs, rice, pasta, potatoes, vegetables (veg. soup); [underlined: “Healthier” (ref)]: Higher in vegetables (veg. soup), fish, and lower in EDF; DP Method(s): Factor or cluster analysis and Latent Class Analysis | Age at outcome: 10 y (F/U: 3 y); PLS-1 and:; - FBG, β: 0.022, 99% CI: −0.016, 0.060; - HOMA-IR, β: 0.047, 99% CI: 0.012, 0.083; PLS-2 and:; - FBG, β: −0.016, 99% CI: −0.046, 0.014; - HOMA-IR, β: −0.015, 99% CI:-0.043, 0.013; PCA-1 and:; - FBG, β: 0.040, 99% CI: −0.005, 0.085; - HOMA-IR, β: 0.054, 99% CI: 0.013, 0.096; PCA-2 and:; - FBG, β: −0.009, 99% CI: −0.052, 0.033; - HOMA-IR, β: −0.017 , 99% CI: −0.056, 0.022; EDF vs. Healthier and:; - FBG, β: 0.028, 99% CI: −0.066, 0.122; - HOMA-IR, β: 0.055 , 99% CI: −0.032, 0.142; Snacking vs. Healthier and:; - FBG, β: −0.009, 99% CI: −0.159, 0.140; - HOMA-IR, β: 0.110, 99% CI: −0.029, 0.249; Summary: Positive: PLS-1 & HOMA-IR; Positive: PCA-1 & HOMA-IR; NS/Null: Other dietary patterns & FBG | - Did not account for: Sex, Race/Ethnicity (Portuguese), Socio-economic Position; - Diet assessment: FFQ once (FFQ validated only in adults but verified by 3-day diary in sub-sample); - Fasted (8-10 hour) blood samples collected; - Authors documented missingness, but magnitude of difference is not high between those that completed vs. non-participating cohort at baseline.; - Funding: Programa Operacional de Saúde (Regional Department of Ministry of Health); Portuguese Foundation for Science and Technology and by the Calouste Gulbenkian Foundation; EDER from the Operational Programme Factors of Competitiveness and national funding (Portuguese Ministry of Education and Science)
Siddiqui, 2022^13^; Netherlands; Generation R Study; Analytic N=3991; Selection data: Enrolled participants at birth; Excluded those with missing FFQ or outcome data | Age at dietary pattern: 8 y; [underlined: Children’s Diet Quality (DQ) Score] [underlined: (CDQS]) [van der Velde, 2018]: Positive: Vegetables; Fruit; Nuts; Whole Grains; Dairy Products; Fish; Oils and fats; Negative: Meat; Sugar-containing beverages;; Method: Index/score | Age at outcome: 10 y; CDQS & FBI, β: 0.01, 95% CI: −0.02, 0.04; Summary: Null: CDQS & FBI | - Did not account for: None (all key confounders were accounted for); - Non-fasting blood samples collected for insulin and blood lipids; - Missingness not clearly accounted for; Funding: Erasmus Medical Center (EMC), the Dutch Ministry of Health, Welfare, and Sports, and the Netherlands Organization for Health Research and Development
Vallejo, 2022^14^; Germany; DONALD (Dortmund Nutritional and Anthropometric Longitudinal Designed) Study; Analytic N=298 final sample; 284 sensitivity analysis; Selection data: Excluded those younger than 15 years; had <2 diet records; missing data; underreported TEI; multiple birth pregnancies; low birth weight; preterm pregnancy; those with a long f/up time | Age at dietary pattern: 15 y and older; [underlined: Dietary index (DI) score from the EAT-Lancet Reference Diet] [Vallejo, 2022]: Positive: Whole grains & all grains, ≤ 464 g/d and whole grain fiber; Tubers or starchy vegetables, ≤ 100 g/d; Vegetables, ≥ 200 − ≤ 600 g/d; Fruits, ≥ 100 - ≤ 300 g/d; Dairy foods, ≤ 500 g/d; Beef and lamb, ≤ 14 g/d; Pork, ≤ 14 g/d; Chicken and other poultry, ≤ 58 g/d; Eggs, ≤ 25 g/d; Fish, ≤ 100 g/d; Dry beans, lentils & peas, ≤ 100 g/d; Soy foods, ≤ 50 g/d; All nuts, ≥ 25 g/d; Palm oil, ≤ 6.8 g/d; Unsaturated oils, ≥ 20 - ≤ 80 g/d; Lard or tallow, ≤ 5 g/d; Butter, 0 g/d; All sweetners, ≤ 31 g/d; Method: Index/score | Age at outcome: 18 y; DI score & FPG; - Continuous: β: 0.99, 95% CI: 0.99, 1.01; p = 0.647; - T1: β: 92.1, 95% CI: 88.9, 95.4; - T2: β: 94.7, 95% CI: 91.5, 98.1; - T3: β: 92.2, 95% CI: 89.0, 95.5; - p = 0.138; Summary: Null: DI score & FPG | - Did not account for: Anthropometry (adjusted for birthweight), Race/Ethnicity, Physical activity; - Diet assessed with 3-day weighted food diaries; - Fasted blood samples collected; - Sensitivity analyses by sex: DI score & continuous Weight (p = 0.036) and continuous BMI (p = 0.020) for males; tertiles & DBP (0.039) for females; After removal of long follow-up: continuous DI score & Weight, BMI, FFMI, WC, Body fat %; Tertiled DI score & BMI; Using standardized kcal/d for males & females: similar results (data NR); - Funding: German Federal Ministry of Education and Research grant, Ministry of Science and Research of North Rhine Westphalia, Germany
Wu, 2021^15^; Finland; YFS (Cardiovascular Risk in Young Finns Study); Analytic N=1007; Selection data: Included those with at least 3 out of 5 observations of diet data; diet and risk factor baseline data; adult FBG or T2D data. Excluded those with T1D or pregnancy in 2001, 2007, or 2011. | Age at dietary pattern: 3 to 18 y; ‘[underlined: Traditional Finnish’]: Positive: rye, potatoes, butter, milk, coffee, sausage. Negative: fruits, berries; [underlined: ‘High Carbohydrate’]: Positive: wheat, margarine and oils, sugar, milk, beef, eggs ‘[underlined: Vegetables and Dairy Products’:]; Positive: vegetables, fruits, cheese, other dairy products, tea, beef, alcoholic beverages. Negative: milk; [underlined: ‘Traditional Finnish and High Carbohydrate’]: Positive: wheat, other grain products, rye, potatoes, butter, sausages, and sugar; ‘[underlined: Red Meat’]: Positive: pork, other meats, sausages, eggs, fish, potatoes, and alcoholic beverages. Negative: tea; [underlined: ‘Healthy’]: Positive: vegetables, legumes and nuts, fruits, fish, cheese, other dairy products, tea, other meats, eggs; Method: Factor or cluster analysis | Age at outcome: ~41-42 y (30.7 y mean f/u duration):; Impaired v. normal fasting glucose (IFG v. NFG) ‘Traditional Finnish ‘; - L-slight decrease, RR: 1.00, ref; - M-slight increase, RR: 1.00, 95% CI: 0.76, 1.31; - H- stable, RR: 1.03, 95% CI: 0.67, 1.58; - High CHO; - M-slight decrease, RR: 1.00, ref; - M-stable/M-large increase, RR: 0.80, 95% CI: 0.62, 1.04; ‘Vegetables and Dairy Products’; - L-moderate decrease, RR: 1.00, ref; - M-stable, RR: 1.01, 95% CI: 0.57, 1.36; - M-moderate increase, RR: 1.00, 95% CI: 0.57, 1.74; ‘Traditional Finnish’ and ‘High Carbohydrate’; - M-stable/M-large decrease, RR: 1.00, ref; - M-slight increase, RR: 0.71, 95% CI: 0.50, 1.01; ‘Red meat’; - L-stable, RR: 1.00, ref; - M-stable/M-large decrease, RR: 1.46, 95% CI: 1.12, 1.90; ‘Healthy’; - L-stable, RR: 1.00, ref; - M-stable/M-large increase, RR: 0.91, 95% CI: 0.69, 1.21; Summary: Positive: ‘Red Meat’ & IFG; NS/Null: & IFG | - Did not account for: Race/Ethnicity; - Diet assessed 5x over 30 y total with 48-hour recall, then changed methods to FFQ; - Fasted blood samples collected; IFG defined as FBG ≥ 5.6 ≤ 6.9 mmol/L; - Funding: Academy of Finland; Social Insurance Institution of Finland; Competitive State Research Financing of the Expert Responsibility area of Kuopio, Tampere and Turku University Hospitals; Juho Vainio Foundation; Paavo Nurmi Foundation; Finnish Foundation for Cardiovascular Research; Finnish Cultural Foundation; The Sigrid Juselius Foundation; Tampere Tuberculosis Foundation; Emil Aaltonen Foundation; Yrjö Jahnsson Foundation; Signe and Ane Gyllenberg Foundation; Diabetes Research Foundation of Finnish Diabetes Association; EU Horizon 2020 Grant; European Research Council; Tampere University Hospital Supporting Foundation; National Health and Medical Research Council Project

Table 7 Risk of bias for randomized controlled trials examining dietary patterns consumed by children and adolescence and risk of type 2 diabetes^a^

Article | Randomization | Deviations from intended interventions (effect of assignment) or (per-protocol) | Missing outcome data | Outcome measurement | Selection of the reported result | Overall
Asoudeh, 2020^1^ | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS

a Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898 31462531 .

Table 8 Risk of bias for observational studies examining dietary patterns consumed by children and adolescence and risk of type 2 diabetes^a^

Article | Confounding | Exposure Classification | Participant Selection | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall
Aljahdali, 2022^2^ | Low | Some concerns | Low | Some concerns | High | Low | High | High
Asghari, 2016^3^ | High | Low | Low | Low | Low | Low | Some concerns | High
Buckland, 2022^4^ | Some concerns | Some concerns | Low | Low | Some concerns | Low | Some concerns | High
Bull & Northstone, 2016^5^ | High | High | Low | Low | High | Low | High | Very high
Chan She Ping-Delfos, 2015^6^ | Some concerns | Low | Low | Low | Some concerns | Low | Some concerns | Some concerns
Costa, 2023^7^ | High | Some concerns | Some concerns | Low | High | Low | Some concerns | High
Durão, 2022^8^ | Some concerns | Some concerns | Some concerns | Low | Some concerns | Low | Some concerns | High
Krijger, 2021^9^ | Low | Low | Some concerns | Low | High | Low | Some concerns | High
Luque, 2021^10^ | Some concerns | Low | Low | Low | Some concerns | Low | High | High
McCourt, 2014^11^ | Some concerns | Low | Low | Low | Some concerns | Some concerns | Low | Some concerns
Pinto, 2020^12^ | High | Some concerns | Low | Low | Some concerns | Low | Some concerns | High
Siddiqui, 2021^13^ | Low | Low | Low | Low | Some concerns | Some concerns | Some concerns | Some concerns
Vallejo, 2022^14^ | High | Some concerns | Low | Low | Low | Low | Some concerns | High
Wu, 2021^15^ | Low | Some concerns | Low | Some concerns | Some concerns | Low | Low | Some concerns

a Possible ratings of low, some concerns, high, very high, not applicable, or no information were determined using the “Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)” tool ( ROBINS-E Development Group, Higgins J, Morgan R, Rooney A . Risk Of Bias In Non-randomized Studies - of Exposure (ROBINS-E). Launch version, 1 June 2022. Available from: https://www.riskofbias.info/welcome/robins-e-tool. )

## Adults and older adults

The 2025 Dietary Guidelines Advisory Committee updates the existing systematic review^*^ by synthesizing an additional 118 articles that were published between January 2014 and May 2023, met inclusion criteria, and assessed how this new evidence relates to the conclusion statement from the existing systematic review. These 118 articles examined the relationship between dietary patterns consumed by adults and older adults and risk of type 2 diabetes using the following study designs:

- 14 articles from 10 randomized controlled trials (RCTs),^16–29^
- 104 articles from observational studies,^30–133^ where all but one analyzed prospective cohort studies and the exception was from a nested case-control study.^111^

* Dietary Patterns Technical Expert Collaborative and NESR Staff. A Series of Systematic Reviews on the Relationship Between Dietary Patterns and Health Outcomes. March 2014. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://nesr.usda.gov/sites/default/files/2019-06/DietaryPatternsReport-FullFinal2.pdf

### Description of the evidence

#### Population

The analytic sample sizes of study groups among RCTs ranged from N=120 up to N=43,232 and among observational studies ranged from N=1057 up to N=357,419. The mean follow-up duration ranged from 12 weeks to 8.5 years among the RCTs and from 6 months to 30 years among observational studies.

##### Health status

Most of the RCTs enrolled participants at high risk for diet-related chronic disease, such as 100% of participants with overweight or obesity, 100% of participants with 3 or more risk factors for metabolic syndrome, or the majority (47 to 67%) of participants with hypertension.^16,19–22,24–27,29^ Among 51 articles from observational studies, the mean body mass index of the study population at baseline was ≥ 25 kg/m^2^ in.^32–34,37–39,41,42,44,48,49,51–54,58,63–66,69,70,72–74,76,81–84,86,89,94,96,98–101,104,107,110,113,118,120,123,126,130–133^

##### Race and/or ethnicity

Racial and/or ethnic composition of the study participants from RCTs was reported in 4 articles as >80% white/Caucasian in 3 articles and 91% non-Hispanic Black, 6% multi-racial, and 3% Native-American in 1 article. Twenty-six articles reported that participants were primarily (≥ 68%) Caucasian or white.^31,37,39,40,42,45,49,64,65,88,89,97–99,102,103,110,113,115,117,121,123,126,130,131,133^

Within studies conducted in the United States, several articles reported diversity among participants from racial and/or ethnic minorities:

- 100% Hispanic/Latino,^93^
- 42% Japanese American, 36% White, 13% Hawaiian-American, 9% other ancestry,^71^
- 26% Japanese American, 2% Hispanic/Latino, 23% White, 16% Black, 7% Native Hawaiian, and 6% other ancestry,^72^
- 62% Black and 38% White,^48^
- 25 to 28% Japanese American, 22 to 24% White, 13 to 19% Black, 10 to 12% Hispanic/Latino, ~7% Native Hawaiian,^73^
- 74 to 92% Black, 5 to 16% Asian, and ~2 to 6% Hispanic,^65^
- 43% White, 25% Black, 21% Hispanic, 11.5% Chinese^100^

About half of all included articles did not report specific data on the racial and/or ethnic composition of participants, but these articles typically indicated ancestry/heritage or country of birth, including 8 articles with a majority/exclusively Australian participants,^33,51,68–70,101,106,122,125^ 7 articles with only Iranian participants^38,58,78,109,119,120^ and 8 articles from studies conducted in only participants of Asian-ancestry (Chinese, Japanese, or Korean).^43,79,86,87,92,111,128^,^114^

##### Socioeconomic position (SEP)

Observational studies included participants from a range of SEP, based on either education, household income, and/or other SEP indicators (e.g., ~29% low, 40% mid, 22% high household income; 31% low, 34% medium, and 35% high scores on the Socio-Economic Indexes for Areas index). In 26 articles from observational studies, participants had higher SEP based on occupation (e.g., all health professionals) or education (e.g., all with at least 12 years or some college). Ten articles did not report information on the SEP of participants.

Studies were conducted in a total of 22 different countries that included multiple articles from the same country as follows: Australia, n=8; Brazil, n=1; Canada, n=1; China, n=1; Croatia, n=1; Denmark, n=4; Finland, n=2; France, n=5; Germany, n=1; Greece, n=4; Iran, n=7; Italy, n=1; Japan, n=1; Korea, n=4; Mexico, n=1; Netherlands, n=8; Peru, 1; Singapore, n=2; Spain, n=9; Sweden, n=4;United Kingdom, n=10; and the United States, n=36. Three articles studied participants across several European countries. Multiple included articles from a single cohort study were included when each article reported unique data, such as different dietary patterns and/or outcomes, as follows:

- ARIC, n=2;
- ATTICA, n=3;
- Australian Longitudinal Study on Women’s Health (ALSWH), n=4;
- BIOBANK, n=7;
- Coronary Artery Risk Development in Young Adults (CARDIA), n=4;
- Danish Diet, Cancer and Health Cohort Study, n=3;
- Etude Epidémiologique auprès de femmes de la Mutuelle Générale de l’Education Nationale (E3N), n=3;
- European Prospective Investigation into Cancer (EPIC) cohorts, n=5;
- The Galiat Study, n=3;
- Health Professionals Follow-Up Study (HPFS) and/or Nurse’s Healthy Study (NHS I, II), n=9;
- Korean Genome and Epidemiology Study (KoGES), n=4;
- Lifelines Cohort, n=4;
- Malmo Diet and Cancer (MDC) cohort, n=4;
- Multi-ethnic Cohort (MEC), n=3;
- NutriNet-Sante, n=2;
- Prevención con Dieta Mediterránea (PREDIMED), n=2;
- Rotterdam Study, n=2;
- Seguimiento Universidad de Navarra (SUN) cohort, n=4;
- Singapore Chinese Health Study, n=2;
- Tehran Lipid and Glucose study, n=6;
- Women’s Health Initiative (WHI), n=9.

#### Intervention/exposure and comparator

Dietary patterns were examined among adults and older adults, primarily between ages 40 to 55 years (range: 18 to 85 years). Dietary patterns were derived from food, beverage, and nutrient data obtained from validated food-frequency questionnaires (n=83), 24-hour recalls (n=9), or diet histories (n=7). Multiple dietary assessments were collected during follow-up in 28 articles, while the rest analyzed data captured at baseline only. Analytic approaches to study dietary patterns included:

- Randomized dietary interventions^16–29^
- A priori index/score derivation,^30,31,33–37,41–56,58,60–63,65–72,75–80,82–85,88–91,94–101,104–110,112,113,116–121,123,124,126,127,129–133^
- Factor/cluster or latent-class analysis,^32,38,54,57,74,81,87,92,93,105,121,122,125,128^
- Reduced rank regression.^38,40,53,64,73,82,86,103,111,114^

Labels or names of dietary patterns varied across studies, with examples including “Mediterranean” style indices, DASH diet scores, dietary guideline-related scores such as the Healthy Eating Index (HEI), plant-based diet indices, “Vegetarian”, “typical Japanese”, and “Western” dietary patterns.

A visualization of all dietary pattern components in each dietary pattern examined in relation to outcomes of interest is available in Appendix 6: Dietary pattern visualization.

#### Outcomes

Studies used various methods to determine outcomes reported, including ascertainment of participants’ diagnoses of type 2 diabetes. Incident type 2 diabetes cases were determined from:

- Fasting blood samples collected clinically using standardized procedures (n=45 articles)
- Self-report of diagnosis or medication usage.^31,33,35,37,40,42,43,45,46,48,50,55,62,63,65,68–73,75,85,87–90,97,98,103,104,106,108,110,113,116,125–127,133^
- Medical records, registries, and/or databases (e.g., drug, health-insurance).^39,76,81,83,84,95,102,115,117,130^
- A combination of self-report, registries, and/or clinical exams.^32,56,57,61,74,77,82,85,94,99,105,118,124,132^

Most articles (e.g., 100 of 103 prospective cohort studies) defined type 2 diabetes using criteria such as the National Diabetes Data Group or American Diabetes Association (ADA) for cut-points of fasting blood glucose≥ 140 mg/dL (7.0 mmol/L), 2-hour value of an oral glucose tolerance test ≥ 200 mg/dL (11.1 mmol/L); ≥2 elevated fasting or non-fasting blood glucose measures on different occasions; HbA1C ≥ 6.5% if after 2010; or current treatment with anti-glycemic agents. The following outcomes were reported across the body of evidence:

- Incident type 2 diabetes, n=104 articles
- Prediabetes,^23,36,44,49,122,131^
- HbA1c,^30,66,96,131,133^
- Fasting blood glucose,^23,49,66,96,118,122^
- Insulin, HOMA-IR,^30,44,72,96,118,120,122,131^

### Synthesis of the evidence

In the majority of evidence, dietary patterns related to lower incidence of type 2 diabetes similarly reflected higher intakes of vegetables, fruits, nuts, legumes, whole grains, fish/seafood and generally low or lower in red and processed meats, refined grains, sugar-sweetened beverages, and sources of added sugars, saturated fat, and sodium (see Appendix). Evidence for this relationship came from the majority of studies that shared a similar direction of findings and magnitude of effect estimates in 75 articles, including 4 articles from 3 RCTs^23−25,27^ and 71 articles from observational studies.^30,32,33,35,39,41–50,55,57,60–63,65–67,69–74,77–85,87,89,92,93,95–99,102,104,105,108–113,115,116,118,121–123,125–128,130–133^ Most of these dietary patterns included alcoholic beverage intake as a positive or moderate contributor to these dietary patterns (~65 of 80 dietary patterns), but few studies analyzed associations from these dietary patterns with and without alcoholic beverages. Few studies scored alcoholic beverage intake negatively (11 articles) or did not include it as a component in the dietary patterns compared. Dairy and/or milk products were often included but considered differently across these dietary patterns, such as including total dairy and/or milk products scored as a negative component compared to specifically low-fat dairy scored positively. The methods and labels for these dietary patterns varied across the body of evidence, including investigator-assigned dietary intervention in the RCTs, a priori indices or scores such as “Mediterranean” style, dietary guideline-related, DASH diet, country-specific, and other scores, as well as a posteriori or hybrid methods (e.g., factor analysis and reduced rank regression), and self-reported ‘vegetarian’ status (e.g. ‘meat eater’) across observational studies.

Four articles from 3 different RCTs reported that participants randomized to intervention diets compared to control diets had reduced risk of type 2 diabetes and/or lowered fasting blood glucose.^23–25,27^ In the Women’s Health Initiative Dietary Modification trial, women randomized to a healthy low-fat dietary pattern of increased vegetables, fruits, grains, fiber, and reduced intake of fat (total and saturated) had a lower risk of developing type 2 diabetes^23^ requiring insulin,^25^ lower risk of prediabetes,^23^ and/or lower fasting blood glucose ^23^ compared to control participants consuming their usual diet. In the PREDIMED study, adults at high-risk for cardiovascular disease, randomized to either of two intervention diets that were abundant in vegetables, fresh fruit and juices, legumes, fish or seafood, nuts and seeds, white meat instead of red or processed meats, cook regularly with tomato, garlic and onion; wine if consuming alcohol; ad libitum eggs, fish, seafood, low-fat cheese, chocolate, whole-grain cereals and either + 15L extra-virgin olive oil or ~ 30g nuts) compared to participants randomized to the low-fat dietary intervention group had statistically lower risk of type 2 diabetes after ~4.8y follow-up.^27^ Pavic et al.^24^ that participants assigned to consume more olive oil, nuts, and fish as part of a ‘Mediterranean’ diet intervention had significantly lowered their fasting plasma glucose to a greater extent compared to those in the standard low-fat diet group, but the groups did not differ in HbA1C.

Dietary patterns derived from various indices/scores were used in the majority of the observational studies, which reported similar results despite variation in the name, label, or style of dietary pattern (e.g., Mediterranean, dietary guideline-related, DASH, “Plant-based”, or other).

- “Mediterranean” style scores were associated with lower type 2 diabetes incidence,^30,35,41–43,55,60,61,63,65,71,72,78,80,96,99,105,108,127,131^ in addition to lower incident prediabetes/type 2 diabetes^,131^ lower HbA1C and insulin resistance,^30^ lower log-serum insulin,^96^ and/or lower HOMA-IR in both men and women.^72^ Similarities across these “Mediterranean” indices included: scoring vegetables (not potatoes), fruit, legumes, nuts, whole grains, fish, and unsaturated vegetable oils/fats as positive components; alcoholic beverages as positive or neutral components; and red and processed meat and sugar-sweetened beverages as negative components. Some of the reported results were sex-specific e.g. significantly lower type 2 diabetes incidence in men but not women,^71,72^ or differed by race/ethnicity.^72^ In addition, “Mediterranean” style scores were not significantly associated with other type 2 diabetes outcomes such as pre-diabetes,^36,131^ HbA1c,^96^ and serum glucose.^96^ No associations were reported between “Mediterranean” style scores and incident type 2 diabetes in 5 articles.^31,36,58,69,70^
- Dietary guideline-related scores were associated with lower risk of type 2 diabetes.^42,43,48,62,67,69–72,84,89,96–98,100,104,113,127^ These scores included variations of the HEI, such as the HEI-2010, HEI-2005, and variations of alternative HEI (AHEI) indices. One study found an inverse relationship between AHEI scores and log-serum insulin, but not with serum glucose.^96^ Similarities across these indices included vegetables (not potatoes/French Fries), fruits, legumes and nuts, whole grains, and sources of unsaturated fats (relative to saturated fats) scored positively, alcoholic beverage intake scored as a neutral component, and red and processed meats, sources of trans/solid and/or saturated fats, added sugars (e.g., sugar-sweetened foods and/or beverages including fruit juice), and sodium each scored negatively. Several (i.e., HEI-2010) scores included total protein foods and seafood/plant proteins scored positively and refined grains negatively. Using the HEI-2010, one study found no association between dietary patterns and type 2 diabetes; however, using AHEI-2010 produced a significant inverse association between dietary patterns and type 2 diabetes incidence.^71^ Racial/ethnic differences in the inverse association between dietary guidelines-related scores and type 2 diabetes incidence were reported in 2 studies.^72,104^ Small to moderate, as well as large, increases in AHEI scores were associated with significantly lower type 2 diabetes incidence,^89^ but some differences by sex were noted when results were stratified. No associations between incident type 2 diabetes were reported in 6 articles.^34,58,68,82,117,129^
- ‘DASH’ style scores were associated with lower type 2 diabetes incidence and/or prediabetes ^131^, or lower HbA1C and fasting plasma glucose ^66^ in 9 articles. ^42,43,65,66,71,72,97,127,131^ All of these “DASH”-style indices scored the following components positively: vegetables (not potatoes), fruit and fruit juice, legumes and nuts, and whole grains; and the following negatively: red and processed meat, sugar-sweetened beverages, and sodium. All but one of these scores included low-fat dairy as a positive component, with the one exception that scored total dairy positively.
- “Plant-based” or plant-focused diet scores were significantly associated with lower risk of type 2 diabetes in all 9 (of 9) articles that examined that type of dietary pattern.^43,45,46,79,85,110,121,126,127^ Lower risk of type 2 diabetes was reported with both the overall plant-based diet score, as well as the healthful version, which positively scores intake of vegetables; fruits; nuts; legumes; whole grains; vegetable oils; tea/coffee, and negatively score intake of any animal-based foods (animal fats; dairy; eggs, fish/seafood; meat (poultry and red meat); and miscellaneous animal-based foods). In the “healthful” version, intakes of fruit juices; sugar-sweetened beverages; refined grains; potatoes; sweets/desserts are also scored negatively scores.
- Other dietary pattern indices/scores related to lower risk of type 2 diabetes showed similar effect direction and size as those described above.^33,43–45,49,50,57,73,77,79,83–85,95,110,115,118,123,126,127,130–132^ Common elements of these dietary patterns included higher intakes of vegetables, fruits, legumes, whole grains (or non-refined cereals), fish and/or seafood; and lower or low intakes of red and processed meat, and sugar-sweetened foods and beverages. Fat intake was often considered as a component, but scored differently across these dietary patterns (e.g., sources of unsaturated fats scored positively and/or other types of fats (e.g., Trans, total) scored negatively. In addition, the specificity of food sources of fat intake varied, with some studies specifying unsaturated vegetable oils, whereas others specified a ratio of intake from unsaturated fatty acids relative to saturated fatty acids. Scoring procedures and specificity of other components varied, particularly among indices that were country- or ethnically-specific, such as rye bread, organ meats, dairy and dairy products, and alcoholic beverage intake. A few of these scores had unique components that were not included across most dietary patterns, such as glycemic index and diversity of fruits and/or vegetables.

Studies using other analytic approaches to identify dietary patterns aligned with the findings from investigator-derived dietary pattern indices/scores. Some sex-specific results or results that were trending in the same direction but did not reach statistical significance were also reported.^57,87,92,102,111,121^ For example, Ericson and colleagues found statistically significant associations between consumption of a dietary pattern (which had high factor loadings for cottage cheese (in women) or cream (in men), fiber-rich bread, vegetables, fruits, breakfast cereals, fish and low-fat yoghurt and low factor loadings for low-fiber bread, red and processed meat, sugar-sweetened beverages) and lower risk of type 2 diabetes in men and women.^57^ Lee and colleagues^87^ reported statistically significant associations between consumption of a dietary pattern in women characterized by vegetables (light-colored, green/yellow), lean fish, seaweeds, mushrooms, shellfish, kimchi, bone fish, pickled vegetables, fruits, tubers, legumes and soy products, milk, yogurt and fatty fish and lower risk of type 2 diabetes in women, but no significant association was reported in men. Ma and colleagues^92^ reported lower incident type 2 diabetes among those consuming a “typical Japanese’ dietary pattern, which was highest in boiled and fermented beans; fish; green vegetables, red/yellow vegetables, white vegetables; fruit; miso soup, rice, tofu, and lowest in bread, fruit juice, vegetable juice; and moderate items included milk, soy milk, yogurt, beef/pork, chicken, ham/sausage. In addition, Tison and colleagues^121^ found that a dietary pattern characterized by vegetables, fruits, beans, poultry, and fish, associated with lower type 2 diabetes risk but results were not statistically significant.

Higher type 2 diabetes incidence was associated with dietary patterns that reflected low or lower intakes of vegetables, fruits, whole grains, nuts, and high or higher intakes of fried potatoes, red and processed meats, refined grains, and sugar-sweetened foods and beverages (often including tea, coffee, and juice) were associated with higher type 2 diabetes incidence in 23 articles.^37,53,54,56,74,75,79,87,88,90,103,106,109,114,116,119–121,125,126,128^ Three articles examined dietary patterns using the Nova classification system for “ultra-processed food (UPF)”. Results from studies using other analytic approaches to examine dietary patterns^64,87,114,128,121^ aligned with those based on index/score derivation. For example, higher risk of type 2 diabetes was associated with various dietary patterns (from either factor/cluster and/or reduced rank regression analyses) that were characterized by:

- ‘Fried foods, organ meats, processed meats, eggs and egg dishes, added fats, high-fat dairy foods, SSBs, and bread^121^
- Fatty fish, pizza/hamburger, processed meats, high-fat red meat, bread, poultry, red meat by-products, cake/snack/cookie, noodles/dumpling, dairy products (in men only), other seafood, carbonated beverages, and red meat ^87^
- Fried food, soft drinks, and desserts^128^
- Lower intakes of vegetables, fruit, whole meal bread, high-fiber cereals low-fat dairy products and higher in fried potatoes, processed meat, white bread, butter and animal fat and added sugar^103^
- Higher intakes of sugary beverages, Added sugar, Juice (plus coffee and savory snacks in men), and lower in Vegetables, Fruits, Nuts/seeds, Cereals, Tea, and Dairy products (low fat, fermented, unsweetened) in men and women (plus Fatty fish, Other Fish, high fat Cheese, Eggs in women or in men, chocolate spreads and bread)^54^
- Higher intakes of chocolate and confectionery, butter, low-fiber bread, sugars and preserves and low intakes of fruit and vegetables^64^

In 30 articles, no associations were reported between dietary patterns and all or most reported measures of type 2 diabetes outcomes.^16–22,26,28,29,31,34,36,38,40,51,52,58,68,76,86,94,100,101,107,117,119,124,129^

### Conclusion statement and grade

The 2025 Dietary Guidelines Advisory Committee updated the existing conclusion statement^*^ (Appendix 2: Conclusion statements from the existing systematic reviews), to answer the question “What is the relationship between dietary patterns consumed and risk of type 2 diabetes?”, based on their review of evidence that examined dietary patterns consumed by adults and older adults. (Table 9)

* A conclusion statement is carefully constructed, based on the evidence reviewed, to answer the systematic review question. A conclusion statement does not draw implications and should not be interpreted as dietary guidance.

Table 9 Conclusion statement, grade for dietary patterns consumed by adults and older adults and risk of type 2 diabetes

Conclusion Statement | Dietary patterns consumed by adults and older adults that are characterized by higher intakes of vegetables, fruits, legumes, nuts, whole grains, and fish/seafood and lower intakes of red and processed meats, high-fat dairy products, refined grains, and sugar-sweetened foods and beverages are associated with lower risk of type 2 diabetes. This conclusion statement is based on evidence graded as strong.
Grade | Strong
Body of Evidence | 118 articles (14 from 10 RCTs; 104 from observational studies) assessed as they relate to the evidence in the existing review (37 articles)
Consistency | Minimal variation in direction and significance of findings
Precision | Interventions demonstrated adequate power/sample sizes. Observational studies had large sample sizes and reported results with narrow confidence intervals.
Risk of bias | Most studies accounted for important confounding domains with few exceptions, such as potential for confounding due to not accounting for family history of diabetes. Few/no concerns with potential for misclassification of the exposure. Serious concerns with only some studies that used only self-report and/or hospital records to determine incident cases
Directness | Few concerns with directness: the populations, intervention/exposure, comparators, and outcomes were directly related to the systematic review question in most studies
Generalizability | Relative to the U.S. population, the participant characteristics, dietary patterns, and outcomes examined in most of the included studies are applicable.

#### Assessment of evidence

The body of evidence includes 118 articles published since 2014, assessed as they relate to the evidence included in the existing review^†^ and examined dietary patterns consumed during adulthood and older adulthood and risk of type 2 diabetes. Dietary patterns were assessed using various (all) analytic approaches, including investigator-assigned dietary interventions, index/score analysis, factor/cluster analysis, latent class analysis, reduced rank regression, and self-reported status as ‘vegetarian’ or ‘vegan’. Incident type 2 diabetes was determined from various methods including self-report, hospital records, registry linkage, and/or fasted blood samples based on standard criteria. As outlined and described below, the body of evidence was assessed for the following elements used when grading the strength of evidence. This body of evidence includes both large and small studies (with significant as well as null findings) so publication bias may be less likely.

† Dietary Patterns Technical Expert Collaborative and NESR Staff. A Series of Systematic Reviews on the Relationship Between Dietary Patterns and Health Outcomes. March 2014. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://nesr.usda.gov/sites/default/files/2019-06/DietaryPatternsReport-FullFinal2.pdf

##### Consistency

The direction of findings was consistent. Several of the RCTs, particularly those conducted in the U.S., reported improvements in blood glucose and/or lower risk of type 2 diabetes/prediabetes among intervention participants who consumed dietary patterns that emphasized vegetables, fruits, nuts, legumes, whole grains, fish/seafood and reflected low or lower intakes of red and processed meats. Most observational studies demonstrated statistically significant effects that were appreciable in magnitude. Many studies supported significant associations between consumption of dietary patterns characterized by high or higher intakes of vegetables, fruits, nuts, legumes, whole grains, fish/seafood and low or lower in red and processed meats, refined grains, sugar-sweetened beverages, and sources of added sugars, saturated fat, and sodium and lower risk of type 2 diabetes and/or prediabetes. A small sub-set of evidence found dietary patterns that were low in vegetables, fruits, whole grains, and nuts, and higher in fried potatoes, red and processed meat; refined grains, and sugar-sweetened beverages were related to higher risk of type 2 diabetes.

##### Precision

Interventions were well-powered; Most observational studies demonstrated statistically significant effects that came from a wide range of sample sizes (N=1,057 up to N=357,419), and demonstrated minimal variance (e.g., narrow confidence intervals).

##### Risk of bias

Studies had numerous risks of bias across domains, which have the potential to influence the reported results. Most articles controlled for most key confounders with exception of family history of diabetes and race and/or ethnicity of participants. Many of the articles may be at higher risk of exposure classification from conducting only single diet assessments and not fully accounting for change in dietary patterns that may occur throughout follow-up. Many of the articles pose higher risk of bias due to outcome measurement from reliance on self-report for incident cases of type 2 diabetes (i.e., may reflect under-estimation) or hospital records (i.e., may reflect more severe cases). Because many of the studies came from observational studies without pre-specified analytic plans and/or conducted multiple exposure and outcome analyses, the body of evidence tended to be at higher risk of bias for selection of reported results.

##### Directness

Most studies were designed to directly examine the relationship between dietary patterns consumed during adulthood and risk of type 2 diabetes.

##### Generalizability

Most studies are applicable to the U.S. population. Many of the articles (e.g., 36 of 104 observational studies) were conducted in the U.S. The body of evidence included studies from a total of 22 countries with similar HDI classification as the U.S. Many participants in this body of evidence had overweight, obesity, or several risk factors for cardiometabolic disease, and therefore, are generalizable to the U.S. population. Younger and older adults were slightly under-represented across this body of evidence, but it is likely that this evidence still generalizes to them. Most dietary patterns compared are applicable to those consumed by Americans, although select dietary patterns and/or isolated components were study- and/or population-specific, e.g. a ‘typical Japanese’ diet; Baltic Sea Diet score, ‘doogh’, fermented and salted seafood, organ meats, kimchi. The outcomes examined are applicable to the U.S. population and include primarily risk of type 2 diabetes incidence as well as various intermediate risk factors such as fasting blood glucose, HOMA-IR, and HbA1C.

Table 10 Evidence in adults and older adults from interventions that examined the relationship between dietary patterns and risk of type 2 diabetes^a^

Article information | Intervention/exposure and comparator | Results | Methodological considerations
Babio, 2014^16^; Spain; PREDIMED; Analytic N=5801; Participant characteristics:; - Health: 100% at high-risk for CVD with at least 3 criteria for Metabolic Syndrome; - Race and/or Ethnicity: NR (Spanish); - SEP:NR | Age at Dietary Pattern: 55 to 80 y; Meditteranean (MED) diet + Nuts, or MED+ extra-virgin olive oil (EVOO), Control diets; [underlined: Med+Nuts]: Abundant olive oil, vegetables, fresh fruit and juices, legumes, fish or seafood, nuts and seeds, select white meat instead of red or processed meats, cook regularly with tomato, garlic and onion; wine preferred (if consuming alcohol); ad libitum nuts, eggs, fish, seafood, low-fat cheese, chocolate, whole-grain cereals; + 15g/d walnuts, 7.5g/d almonds, and 7.5g/d hazelnuts; [underlined: Med+EVOO:] Abundant olive oil, vegetables, fresh fruit and juices, legumes, fish or seafood, nuts and seeds, select white meat instead of red or processed meats, cook regularly with tomato, garlic and onion; wine preferred (if consuming alcohol); ad libitum nuts, eggs, fish, seafood, low-fat cheese, chocolate, whole-grain cereals + 15L EVOO; [underlined: Control:] Advice to reduce dietary fat; Methods: RCT | Follow-up: 4.8 y, median; [underlined: Glucose:] % at f/u with High FPG: 68.9 v. 68.4 v. 71.9; p= 0.03; Summary: NS/Null: Med+EVOO v. Med+Nuts v. Control & High FPG | - Diet assessment: MEDAS screener; - Outcomes: High FPG based o FBG ≥ 100 mg/dL; - Note that the primary data from PREDIMED were included in the existing review and remained the same after republication in 2018 due to randomization errors (both Med diets v. Control & T2D: HR: 0.47, 95% Cl: 0.26, 0.87); Funding: Instituto de Salud Carlos III
Bruno, 2020^17^; Italy; Fondazione IRCCS Istituto Nazionale dei Tumori di Milano; Analytic N=416; Participant characteristics: Health:; - 100% ♀ who were carriers of or had mutations in BRCA1/2; - Weight (kg): IG: 62.1 ±110.7; CG: 65.6±14.6; - BMI(kg/m2): IG: 23.9 ± 4.4, CG:24.7 ± 5.1; - WC (cm): IG: 77.1 ± 11.7, CG:79.0± 13.5; Race and/or Ethnicity: NR (Italian); SEP: Education: 1^st^ level ~ 17%; 2^nd^ 44%; 3^rd^ level 39%; Excluded those who dropped out; changed mind; metastases; pregnancies; variant of uncertain pathogenic significance; >70 years; had a medical condition after randomization; relapses; no final data | Age at Dietary Pattern: ♀ 18 to 70 y at baseline; Mediterranean Diet Adherence Screener (MEDAS) [Schroder 2011], [underlined: Intervention group (IG) vs. Control group (CG)]; [underlined: MEDAS,] Positive: Vegetables; Dishes with Tomato Sauce (tomato, garlic, onion, leek, olive oil); Pulses; Fruit; Nuts; Fish; White Meat Over Red Meat; Olive Oil; Olive Oil as Principal Cooking Fat; Red Wine. Negative: Commercial Pastries; Red Meat or Sausages; Animal fat; Sugar-Sweetened Beverages; Methods: Index/RCT | Follow-up: 6 months; [underlined: Glucose:] mean [SD1; IG at B: 101.2 [22.0]; 6mo: 93.8 [18.3]; p<0.001; CG at B: 101.4 [24.5]; 6mo: 92.5 [19.5]; p<0.001; Δ IG vs. CG: −7.4 vs. −8.8; p=0.51; [underlined: Insulin:] mean [SD]; IG: B: 21.3 [18.7]; 6m: 13.5 [11.6]; p<0.001; CG: B: 20.2 [16.9]; 6m: 14.7 [12.2]; p<0.001; IG:-7.7 vs. CG: −5.5; p=0.11; Summary: NS/Null: IG vs. CG & Δglucose or Δinsulin after 6mo | - Diet assessment: MEDAS screener and 24-h (FF) diary; Funding: Italian Association of Cancer Research; Italian Ministry of Health
Calvo-Malvar, 2021,^18^; Spain; Galiat study; Analytic N=661; Participant characteristics:; Health: CVD, 16–18%; DM, 6%; Race and/or Ethnicity: 100% Caucasian; SEP: Employed ~48–52%; Retired ~14–20%; Other ~32–34%; - Education: None, ~10%; Elementary, 36–42%; Secondary 32–36%; Uni+ 16–18%; - Marital status: Partnered 68–73%;Separated/Divorced/Wid owed 19–10%; Single 21–17%; Included a random representative sample from Spanish National Health System Register (ages 18 to 85 years) and their relatives who shared home as a family unit of ≥2 members. Excluded those with alcoholism, pregnancy, major CVD, dementia, predicted survival of <1 y; using lipid-lowering medication. Analyses include both an intention-to-treat (ITT) with imputed data for missing values, and per-protocol (PP). | Age at Dietary Pattern: ~39y, mean (3 to 85 y at baseline); Atlantic Diet vs. Control; [underlined: Atlantic Diet Intervention Group], Positive: breads, cereals, wholegrain cereals, rice, pasta, potatoes, olive oil, fruit, vegetables, dairy products, nuts (preferable chestnuts and walnuts), fish and seafood, eggs, lean meat, pulses. Negative: fatty meat, cured sausage, margarine, butter, sweets, pastries, cakes, ice cream; [underlined: Control Group]: usualy dietary pattern; Methods: RCT | Follow-up: 6 months; [underlined: HbA1C:] ITT, ∆HbA1c, β: −0.02, 95% CI: −0.05, 0.02; p-trend=0.343; PP, ∆HbA1c, β: −0.02, 95% CI: −0.05, 0.02; p-trend=0.298; [underlined: Glucose:] ITT ∆ FBG, β: 0.4, 95% CI: −1.0, 1.8; p-trend=0.563; PP ∆ FBG, β: −1.0, 95% CI: −2.2, 0.3; p-trend=0.132; [underlined: Insulin:] ITT, ∆Insulin, β: −0.46, 95% CI: −1.12, 0.24p-trend=0.189; ITT ∆HOMA-IR, β: −0.09, 95% CI: −0.24, 0.08; p-trend=0.297; PP ∆Insulin, β: −0.43, 95% CI: −1.09, 0.28; p-trend=0.230; PP ∆HOMA-IR, β: −0.08, 95% CI: −0.24, 0.00; p-trend=0.324; Summary: NS/Null (ITT or PP): Atlantic vs. Control & ∆Fasting Glucose, ∆HbA1c, ∆Insulin, ∆HOMA-IR | - Diet assessment: 3-day food record; - Primary outcomes were body-weight and lipid related; FPG/HOMA-IR were secondary results; Unclear reporting of data in adults vs. children;; - No adjustment for multiple testing was conducted; ITT group includes imputed data; - All participants were from a rural community; Funding: ERDF-Innterconecta for Galicia Program
Georgoulis, 2020; 2021 and 2023^19–21^; Greece; MIMOSA; Analytic N=180; Participant characteristics:; Health: Mean BMI 35.4, 79% Ob; 61% MetS; 77% severe OSA; 75% male & low-PA; Race and/or Ethnicity: NR; SEP: Income: 38% low, 46% medium, 16% high; Included those with BMI ≥25, obstructive sleep apnea (≥15 events/h sleep); Excluded those with central SA; sleep disorders; chronic disease, psychiatric disorders; hospitalization due to acute or chronic respiratory disease or required oxygen during last year; sugery in <3 months; pregnancy or breastfeeding; use of antipsychotic, antidepressant, or other hypnotic drugs; use of steroids or HRT (♀); habitual excessive alcohol intake; on weight loss diet or recent change in lifestyle habits | Age at Dietary Pattern: 49y, mean (18–65y); Mediterranean Diet Score (MedDietScore) [Panagiotakos, 2007]:; [underlined: MedDietScores] were higher in the Mediterranean diet group (MDG) v. Standard Care Group (SCG): Positive: fruits, vegetables, grains (preferably whole grains), dairy, fish & seafood, white meat, legumes, olive oil. Negative: red meat, processed meat, sugar, salt. Moderate alcohol; [underlined: SCG]: Written advice for a healthy lifestyle and an indicative hypocaloric daily dietary plan, i.e., 1800 kcal for ♂ and 1500 kcal for ♀; CPAP prescription; [underlined: MDG]: high consumption of olive oil, vegetables, legumes, whole grains, fruits and nuts, moderate consumption of poultry, fish and dairy products, low consumption of red meat products and sweets, and low-to-moderate consumption of wine; 7, 60-min group counselling sessions, biweekly for the first two months and monthly for the next four months; based on cognitive behavioral therapy; CPAP device; Methods: RCT/Index | Follow-up: 12 months; [underlined: Glucose:]; FBG,; 6mo, −0.26, 95% CI: −0.47, −0.05, P=0.006; P after Wt adjusting=0.1; 12mo, −2.77, 95% CI: −6.06, 0.53, p-trend>0.999; Hyperglycemia; 6mo, RR 0.68, 95% CI: 0.39, 1.19, P=0.3; P after Wt adjusting=0.7; 12mo, RR: 0.80, 95% CI: 0.46, 1.39, p-trend=0.800; [underlined: Insulin:]; 6mo −24.4, 95% CI: −47.1, −1.64, P=0.002; P-adj=0.7; 12mo, −3.08, 95% CI: −5.95, −0.22, p-trend=0.428; [underlined: HOMA-IR:]; 6mo, −1.10, 95% CI: −2.10, −0.10, P=0.001; P-adj=0.5; 12mo, −0.85, 95% CI: −1.67, −0.04, p-trend=0.489; Summary: NS/Null: MDG vs. SCG & glucose, insulin, HOMA-IR, hyperglycemia | - Diet assessment: MedDietScore; - Outcomes: Hyperglycemia (≥5.6 mmol/L or ≥100 mg/dL or taking anti-DM meds); - All participants had obstructive sleep apnea (may be less generalizable); MDG vs. SCG & DBP, hsCRP, presence of MetS, insulin, and HOMA-IR were significant in analyses that do not control for Δbody weight; No true control/placebo group; High attrition rate (e 35% for SCG, 29% for the MDG); No record of feedback on intervention; No adjustment for multiple testing; includes imputed data; SCG did not include CPAP device; ITT and per-protocol analyses generated similar results in different publications.; - No significant differences were observed between completers (n=127) v. dropouts(n=53) in age, sex, education, financial and employment status, dietary, physical activity and sleep habits, or body weight status, AHI and OSA severity, presence of the MS (all p≥0.1).; - Both intervention arms had high participation rate in the counselling sessions (mean number of attended sessions, MDG: 6.38 ± 0.66, MLG: 6.58±0.62, P=0.2).; Funding: Department of Nutrition and
Gotfredsen, 2021^22^; Denmark; Diet and Prevention of Ischemic Heart Disease: a Translational Approach (DIPI); Analytic N=186; Participant characteristics:; Health: 100% with 1+ risk factors (BMI 25+; WC 80cm/94cm; Physically inactive); - Overweight: 51%, 56%, 51% (HAB, SUB, OFF); - Obesity: 16%, 22%, 21% (HAB, SUB, OFF); Race and/or Ethnicity: 100% Danish (NR); SEP: Education (HAB, SUB, OFF):; - ≤HS, 22%, 26%, 29%;; - Associate 11%, 8%, 6%;; - Undergrad. 37%, 42%, 40%;; - Grad 30%, 24%, 25%; Excluded smokers; those pregnant, planning to become pregnant, or breastfeeding; history of chronic diseases that could affect study results; drug abuse; regular alcohol consumption | Age at Dietary Pattern: 30 to 65 y; SUB DG vs. OFF groups; [underlined: SUB DG group]: Targeted substitution dietary guidance, “Eat fruit instead of candy and cake; Eat coarse vegetables instead of fine vegetables; Eat fish instead of red meat; Eat whole grain products instead of products with no whole grains; Eat unsaturated fat instead of saturated fat”; [underlined: OFF group]: Official Danish dietary guidance, “Eat a variety of foods, but not too much, and be physically active; Eat fruits and many vegetables; Eat more fish; Choose whole grains; Choose lean meats and cold meats; Choose low-fat dairy products; Eat less saturated fat; Eat foods with less salt; Eat less sugar; Drink water”; [underlined: HAB group]: habitual intake (no intervention); Methods: RCT | Follow-up: 6 months; [underlined: HbA1C:]; SUB DG vs. HAB; 6mo, β: −0.001, 95% CI: −0.08, 0.07; 12mo, β: 0.003, 95% CI: −0.07, 0.08; OFF vs. HAB; 6mo, β: 0.01, 95% CI: −0.07, 0.08; 12mo, β: 0.06, 95% CI: −0.01, 0.13; [underlined: Glucose:]; SUB DG vs. HAB; 6mo, β: 0.06, 95% CI: −0.05, 0.18; 12mo, β: −0.01, 95% CI: −0.13, 0.10; OFF vs. HAB,; 6mo, β: 0.03, 95% CI: −0.08, 0.15; 12mo, β: 0.04, 95% CI: −0.07, 0.16; [underlined: Insulin:]; SUB DG vs. HAB:; 6mo, β: −2.56, 95% CI: −12.37, 7.25; at 12mo, β: −2.09, 95% CI: −11.66, 7.48; OFF vs. HAB:; 6mo, β: −2.29, 95% CI: −12.00, 7.42; 12mo, β: 3.58, 95% CI: −5.95, 13.10; Summary: NS/Null: SUB DG vs. HAB & HbA1c, Glucose, Insulin NS/Null: OFF vs. HAB & HbA1c, Glucose, Insulin | - Diet assessment: 7-day food record at baseline, 6 months, 12 months; - Intervention was not well-controlled (i.e., weak); Funding: Danish Council for Strategic Research
Howard, 2018^23^; USA; Women Health Initiative (WHI) Dietary Modificantion Trial Analytic N=47,023 total; No baseline T2D: 45,579; Baseline T2D: 1,444; Subsample: 2324; Participant characteristics:; - Health: BMI, kg/m2: 28.9 ± 5.8 v. 28.9 ± 5.8; - WC≥88cm: 47.3% v. 47.8%; - Family history of diabetes: 32.8% v.33.3%; - prior CVD: 3.1% v. 3.2%; - Smoking, Never: 51.4% v. 51.8%; Past: 41.9% v. 41.3%; - Tx for HTN: 33.0% v. 33.8%; - Insulin, uIU/mL: 10.0 ± 6.9 v. 10.0 ± 7.1; - Glucose, mg/dL, median (IQR): 93.0 (15.0) v. 93.0 (12.0); - No significant differences between the randomization groups; - Race and/or Ethnicity: White: ~82.5%; Black: 9.9%; Hispanic: 3.7%; American Indian: 0.4%; Asian/Pacific Islander: 2.2%; - SEP: NR; Excluded ♂, those with prevalent diabetes, reported insulin use during F/U without preceding or concurrent use of oral agents | Age at Dietary Pattern: 62y (no T2D at baseline); 64y (with T2D at baseline); enrolled 50 to 79 y; [underlined: Low-fat diet group]: Decreased fat intake (20% of calories), reduced saturated fat to 7% of total energy, and increased vegetable/fruit (five servings per day) and grain (six servings per day) consumption; [underlined: Control group]: no dietary guidance, received only printed; health-related materials; Methods: RCT | Follow-up: 17.3 y median, T2D; [underlined: Risk of T2D]:; T2D requiring pills in Intervention phase, HR: 0.95, 95% CI: 0.88, 1.02, p-trend=0.13; Intervention + postintervention, HR: 0.96, 95% CI: 0.91, 1.00, p-trend=0.07; T2D requiring insulin; N=45,579 Intervention, HR: 0.74, 95% CI: 0.59, 0.94, p-trend=0.01; Intervention + postintervention, HR: 0.88, 95% CI: 0.78, 0.99, p-trend=0.04; No baseline T2D requiring pills in F/U, progression to T2D requiring insulin; N=45,579; Intervention: HR: 0.82, 95% CI: 0.64, 1.04, p-trend=0.10; Intervention + postintervention, HR: 0.95, 95% CI: 0.84, 1.09, p-trend=0.49; [underlined: Prediabetes]: subsample FBG < 100 mg/dl, OR: 0.75, 95% CI: 0.61, 0.93; P=0.008; [underlined: Glucose:] subsample (average of 1, 3, 6y): Intervention: 94.9 mg/dl; Comparison: 96.3mg/dl; P<0.001 ratio of geometric means: 0.98, 95% CI: 0.98, 0.99, P<0.001; Summary: Inverse: Low-fat diet v. control & T2D, preT2D, FBG | - Did not account for: Alcohol, SEP; - Diet assessment: FFQ periodically (no ∆8y in comparison group; 1.1 serv/d increase in grains in Intervention group); - Outcome: Self-report, agreed with FBG measured in 5.8% subsample and 79% concordant with F/U medication inventory; - Adjusting baseline weight and weight change for T2D requiring insulin: HR 0.73, 95% CI: 0.57, 0.93; P=0.009; - Compliance in intervention group, mean fat intakes decreased by 8.2%, with simily decreases in saturated 2.9% kcal, MUFA 3.3% kcal, PUFA 1.5% kcal; 1.1-serving/day increase in vegetable/fruit intake, 0.5serving/day increase in grains, and an 8.1% increase in total CHO intake; no change in the comparison group.; - Outcomes were not among the designated trial outcomes; glucose measures only available for a subset; info regarding DM medication incomplete;; - Data on n=1444 subset that was exclusively being Tx for T2D at baseline [HR 0.92, 95% CI: 0.75, 1.14, p-trend=0.47; Cumulative, HR: 0.89, 95% CI: 0.75, 1.06, p-trend=0.21]; - Funding: NHLBI; NCI; National Center for Advancing Translational Science of the NIH
Pavić, 2019^24^; Croatia; Other:; Analytic N=124; Participant characteristics:; Health: 100%; Obesity/Overweight; Race and/or Ethnicity: NR; SEP: Education: 42% v. 27% uni+; Employment: 59% v. 37%; Married: 67.2% v. 67.2%; Excluded newly diagnosed diabetes, hypertension or cardiovascular disease, or change in antihypertensive and oral antidiabetic therapy in the period of 3 months prior to the commencement of the study, insulin use, abuse of alcohol or drugs, pregnancy or lactation and use of drugs affecting weight control | Age at dietary pattern: 18–69 y; [underlined: Mediterranean diet (MD):] Increased intake (but NS) of olive oil, nuts, and fish vs. SHD; Assigned to nutrition education, behavior therapy, exercise, and MD: vegetables (2–3 servings/day), fresh fruits (3 servings/day), whole grains (e.g. non-refined cereals, whole-grain bread, pasta etc.), non-fat or low-fat dairy products (1–2 servings/day); low in red meat, with poultry and fish (3–4 servings/week) replacing pork, beef and lamb; energy intake restricted to an average of 1573 kcal/d; 3–4 portions of fish per wk, nuts handful/d (56 g/wk) and 2 tablespoons (corresponding to 30 ml) of EVOO/d provided at the study entry.; [underlined: Standard Hypolipidemic Diet (SHD)]: Lower but NS in olive oil, nuts, and fish vs. MD; Assigned to nutrition education, behavior therapy, exercise, and SHD: whole grains, fruit (3 servings/d), vegetables (2–3 servings/d), restricted additional fats, sweets and high-fat snacks with energy intake limited to 1287 kcal/day; recommended non-fat or low-fat dairy products (1–2 servings/d), legumes (4 servings/wk); Encouraged fish if already part of a regular diet but <1/weekly; Reduce salt; Methods: RCT | Follow-up: 12 months; [underlined: HbA1C:] T0-T12, mean [SD]; HbA1C, %,; MD: 0.1 [0.6], P=0.551; SHD: 0.13 [0.7], P=0.258; MD vs SHD: P=0.214; [underlined: Glucose:] T0-T12, mean [SD]; FPG, mmol/l; MD: 0.6 [0.9], P=0.001; SHD: 0.45 [1.3], P=0.026; MD vs SHD: P<0.001; Summary: Inverse: MD, SHD & FPG (MD more than SHD); Null: MD, SHD & HbA1C | - Diet assessment: FFQ; - Primary outcome Metabolic Syndrome parameters, including BG; Drop-out rate: 33.1%, reasons included lack of motivation and/or unwillingness to continue, health related issues, pregnancy, death and unknown reasons; Adherence to recommendation was “satisfactory”: increase intake in olive oil, nuts, fish in MD group; Intake of red or processed meats, sweets, sweetened beverages and alcoholic drinks decreased from baseline (table 7); Co-interventions possible with physical activity and dietetic supervision; Funding: Grant (Not specified)
Prentice, 2019^25^; USA; WHI; Analytic N=43,232 (w/o prior CVD); 48,835 total; Participant characteristics:; - Health: BMI, 28.2 (mean); Tx: 4% DM, 47% HTN or high-BP, 12% high-cholesterol, 6% on statins; 2% MI, 100% post-menopausal, free of cancer at entry; - Race and/or Ethnicity: 81% White, 11% Black, 4% Hispanic, 0.5% American Indian, 2% Asian/Pacific Islander, 1.4% Unknown; - SEP: Education: 78% ≥HS diploma/GED;; - Family Income. 39% ≥$50K/y; Included postmenopausal ♀ aged 50–79 y with no prior history of breast or colorectal cancer, and with dietary fat intake estimated using an FFQ to be ≥ 32% of total energy intake. Excluded prior history of invasive breast cancer or colorectal cancer, any cancer except nonmelanoma skin cancer within the previous 10 y. | Age at Dietary Pattern: 62.3y, mean (50 to 79 y); [underlined: Intervention]: Increased vegetable, fruit, grain intakes (fiber & carotenoid) and decreased total fat compared to control group; Advised to reduce fat from ~35% of energy at baseline to 20% energy+ increase in veg, fruits, grains; vegetables (2.6 c), fruits (2.5 c) and total grains (5.4 c): whole grain: 1.4 c; other grains 4.0; Provided 18 dietary behavioral sessions in groups of 8–15 and 1 indiviudal session in 1st year, then quarterly group sessions throughout a median 8.5 y; [underlined: Control:] Written health-related materials; veg (2.1 c); fruits (1.8 c); total grain (4.7 c): whole-grain: 1.1 c; other grain: 3.6 c; Methods: RCT | Follow-up: 8.5y, median F/U; [underlined: Risk of T2D]:; Intervention Phase; - DM req. oral agent: HR 0.94, 95% CI: 0.88, 1.01, P=0.11; - DM req. insulin: HR 0.74, 95% CI: 0.58, 0.94, P=0.01; F/U, cumulative; - DM req. oral agent: HR 0.95, 95% CI: 0.91, 1.00, P=0.06; - DM req. insulin: HR 0.87, 95% CI: 0.77, 0.98, P=0.02; Summary: Inverse: Intervention vs. control group & DM requiring insulin (Iv phase & f/u); Inverse, NS: Intervention vs. control group & DM requiring oral agents (f/u phase); Null: Intervention vs. control group & DM requiring oral agents (Iv phase) | - Did not account for: RCT; - Diet assessment: repeat FFQ; - Outcome: T2D based on self-report with verification; - At 1 y, intervention group had lower total energy from fat (~11% similar saturated or unsaturated fats), higher carbohydrate (~10%), protein (~1%), vegetables and fruit by 1.2 to 5.1 serv./d, and grains was higher by 0.7 to 5.4 serv./d.; - Only ~70% of the targeted difference in percentage of energy from fat was achieved; grain servings were lower than the recommened 6/d; self-reported FFQ; multiple testing; unblinded trial; Funding: NIH; NHLBI
Reidlinger,2015^26^; United Kingdom; Cardiovascular disease risk REduction Study (CRESSIDA); Analytic N=162; Participant characteristics: DG v. CG; Health:; - Non-smokers, mean BMI 25.5 v. 26.8;; - mean WC 98 v. 97 cm;; - 50% v. 56% post-menopausal; Race and/or Ethnicity:; - White: 87% v. 80%; - Black: 7% v. 8%; - Asian: 7% v. 8%; SEP: NR; All with BMI 25 to 35, −20% ethnic minority; Excluded those with CVD or >20% 10y CVD risk; chronic disease; History of substance abuse; pregnancy; fluctuation in weight >3 kg in the past 2 months | Age at dietary pattern: 40 to 70 y; [underlined: “Dietary Guidelines” DG diet]: Increased Vegetables and Fruit; Whole Grains; Oily Fish; Reduced Total Fat; SFA; Sodium; Added Sugars; Advice to choose Low-fat Dairy; Lean Meat; and Limit Meat; Meat products, SSBs; Salt; Confectionary, Snacks; Moderate alcohol; [underlined: Control]: traditional British diet without sugar/salt restrictions: Higher in Refined Cereals; Potatoes; Meat; Moderate in Whole Grains, Oily Fish; Advice to consume Vegetables, Fruit, Full-Fat Dairy and Limit Confectionary, snacks; Moderate alcohol; Methods: RCT | Follow-up: 12 weeks; [underlined: Glucose]: FPG, −1%. 95% Cl: −3, 1: p=0.397; [underlined: Insulin]: FBI, 9.6%, 95% Cl: −21.6, 21.5;p=0.12; Summary: NS/Null: DG v. Control & FPG or FBI | - Diet assessment: 4d food record; FFQ before randomization and end of intervention phase; Funding: UK Food Standards Agency and Department of Health and by the National Institute for Health Research (NIHR) Clinical Research Facility at Guy’s and St Thomas’ NHS Foundation Trust and NIHR Biomedical Research Centre based at Guy’s and St Thomas’ NHS Foundation Trust and King’s College London
Salas-Salvado, 2014^27^; Spain; PREDIMED, sub-set; Analytic N=3541 (273 T2D cases at F/U); Participant characteristics:; - Health:100% at-risk for CVD; - Race and/or Ethnicity: NR (100% Spanish); - SEP: Education level, primary: ~72–76%; Secondary ~16%; Graduate ~8%; Married status: ~77%; Included community-dwelling ♂ age 55–80 years and ♀ at 60–80 years without prior CVD but having at least three cardiovascular risk factors (smoking, hypertension, dyslipidemia, overweight, family history of premature CVD); Included only confirmed diabetes events; Excluded participants with diabetes at baseline, and participants who lacked data on diabetes | Age at Dietary Pattern: 55 to 80 y; [underlined: Med+EVOO]: Abundant olive oil, vegetables, fresh fruit and juices, legumes, fish or seafood, nuts and seeds, select white meat instead of red or processed meats, cook regularly with tomato, garlic and onion; wine preferred (if consuming alcohol); ad libitum nuts, eggs, fish, seafood, low-fat cheese, chocolate, whole-grain cereals + 15L EVOO; [underlined: Med+Nuts]: Abundant olive oil, vegetables, fresh fruit and juices, legumes, fish or seafood, nuts and seeds, select white meat instead of red or processed meats, cook regularly with tomato, garlic and onion; wine preferred (if consuming alcohol); ad libitum nuts, eggs, fish, seafood, low-fat cheese, chocolate, whole-grain cereals; + 15g/d walnuts, 7.5g/d almonds, and 7.5g/d hazelnuts; [underlined: Control]: Advice to reduce dietary fat; Methods: RCT | Follow-up: 4.1 median (IQR 2.5–5.7), T2D; [underlined: Risk of T2D]: MedDiet+EVOO vs Control: HR: 0.60, 95% CI: 0.43, 0.85; MedDiet+Nuts vs. Control: HR: 0.82, 95% CI: 0.61, 1.10; Both MedDiets vs. Control, HR: 0.70, 95% CI: 0.54, 0.92; Summary: Inverse: Either Med+EVOO, or Med+nuts, or both Med diets vs. Control & T2D | - Diet assessment: Adherence assessed at each annual f/u visit; - Outcomes: New T2D based on ADA criteria & medical records (FPG ≥ 126 mg/dl (7 mmol/l) or 2-h post 75-g glucose load ≥ 200 mg/dl (11.1mmol/l)); - No restrictions on TEI or PA were made; Results were consistent among subgroups of sex, age, presence of comorbid conditions, smoking status, family history of CVD, and several indices of adipostiy. Sensitivity analyses by including multiple imputations for participants without contact for 2 y or longer and for those who lacked repeated measurements of glucose control yielded similar results as primary finding.; - Note that the primary data from PREDIMED were included in the existing review and remained the same after republication due to randomization errors (both Med diets v. Control & T2D: HR: 0.47, 95% CI: 0.26, 0.87); - Greater loss to follow-up in the control group and worse CVD risk profile among those who withdrew, suggesting a bias toward benefit in the control group; - Funding: Instituto de Salud Carlos III^*^; * Salas-Salvado, 2014 additional funding: Centro de Investigacion Biomedica en Red de Fisiopatologı´a de la Obesidad y Nutricio´n and by grants from Centro Nacional de Investigaciones Cardiovasculares, Fondo de Investigacio´n Sanitaria–Fondo Europeo de Desarrollo Regional, Ministerio de Ciencia e Innovacio´n, Fundacio´n Mapfre 2010, Consejerı´a de Salud de la Junta de Andalucı´a, Public Health Division of the Department of Health of the Autonomous Government of Catalonia, Generalitat Valenciana, Agencia Canaria de Investigacio´n, Innovacio´n y Sociedad de la Informacio´n-EU FEDER, and Regional Government of Navarra. The Fundacio´n Patrimonio Comunal Olivarero and Hojiblanca (Malaga, Spain), California Walnut Commission (Sacramento,California), Borges (Reus, Spain), and Morella Nuts (Reus,Spain).
Sidahmed, 2014^28^; United States; Healthy Eating for Colon Cancer Prevention Study; Analytic N=120; Participant characteristics:; Health: 64% family history of CRC, 27% history adeoma, or 9% both; Race and/or Ethnicity: 88% Caucasian; SEP: NR; Excluded those on a medically prescribed diet/require diet counselling, or on a Mediterranean or low-fat diet already; Enrolled those with one 1st- or 2, 2nd-degree relatives with CRC/polyps; generally healthy, at least 21 y, BMI between 18.5 and 35 | Age at Dietary Pattern: 53 y, mean; [underlined: ‘Healthy eating’ arm]: Assiqned to consume Fruit 2 serv/d, Vegetables 2 serv/d, Dark green or orange vegetables 1 serv/d, Whole grains >3 serv/d, SFA <10% Total E; [underlined: ‘Mediterranean’ arm:] Assiqned to consume Fruit (vit. C) 1 serv/d, Fruit (Other) 1 serv/d, Allium vegetables 1–2 serv/d, Dark green vegetables 1–2 serv/d, Orange and yellow vegetables 1–2 serv/d, Red vegetables 1–2 serv/d, Other vegetables 1–2 serv/d, Dark green herbs 1 serv/d, Whole grains >3 serv/d, High MUFA foods 7–10 exchanges/d, High n-3 foods 3 oz, twice/wk; Methods: RCT | Follow-up: 6mo; [underlined: Insulin:] Effects were NS on measures related Insulin status (Data NR); Summary: NS/Null: ‘Mediterranean’ vs. ‘Healthy-eating’ arms & Insulin | - Diet assessment: 2d records + 24h-recall; - Compliance with assigned interventions was differential (low) at 6mo: Healthy 67% v. Mediterranean 32% compliant with meeting 100% of dietary goals; Healthy 89% v. Mediterranean 85% compliant with meeting ≥7 0% of dietary goals; Funding: NIH; Cancer Center Support
Tussing-Humphreys, 2022^29^; United States; Building Research in Diet and Cognition study; Analytic N=100; Participant characteristics:; Health: 100% OW/Ob; 67% HTN; Race and/or Ethnicity: 91% non-Hispanic, Black; 3% Native American; 6% Multi-racial; SEP: 22% <$20K, 23% $20$40K, 54% >$40K; 99% healthinsured;: Degree: 30% graduate, 20% college, 10% associate; 25% single; 28% married; 16% widowed; 31% divorced; Included if BMI 3–50; Cognitive Assessment score ≥19; MedDiet score <50% adherence; Englishspeaking. Excluded if: inability to exercise; HbA1c >9%; severe chronic, autoimmune, neurologic conditions; on Warfarin; recent or pending bariatric surgery; in weight loss program; in cognitive research in past year comparator | Age at Dietary Pattern: 55 to 85 y; [underlined: MedDiet Score [Tangney 2011]:] Positive: Non-refined grains, potatoes, fruit, vegetables, legumes and nuts, fish, olive oil. Negative: Red meats, poultry, full-fat dairy. Moderate: wine, alcohol; [underlined: MedDiet Group:] Higher MedDiety v. Control at 8mo F/U; Assigned to follow MDS recommendations, maintain body Wt and PA; Increased by F/U; [underlined: Control Group]: No dietary recommendation provided; Health education materials provided weekly. No change in MedDiet score by F/U, but lower MDS than MedDiet at F/U; Methods: Index, RCT | Follow-up: 8mo; [underlined: HbA1C:] mean ∆; MedDiet, −0.1, 95% CI: −0.2, 0.0; Control, −0.0, 95% CI: −0.2, 0.1; between groups, p-trend=0.72; [underlined: Glucose:] mean ∆; MedDiet −0.9, 95% CI: −6.7, 4.8; Control, −5.9, 95% CI: −13.6, 1.8; between groups, p-trend=0.51; [underlined: Insulin:] mean ∆; MedDiet, −0.6, 95% CI: −1.6, 0.4; Control, −0.5, 95% CI: −1.8, 0.8; between groups, p-trend=0.046; [underlined: HOMA-IR:] mean ∆; MedDiet, −0.2, 95% CI: −0.4, 0.1; Control −0.2, 95% CI: −0.6, 0.1; between groups, p-trend=0.08; Summary: NS/Null: Diet Group & ∆HbA1c, ∆Glucose, ∆Insulin or HOMA-IR | - Did not account for: Smoking; - Diet assessment: MedDiet adherence; - Primary outcomes were cognitive/executive function (T2D secondary); MedDiet group advised to maintain weight; No differences in self-reported physical activity at follow-up between groups; Funding: NIH

a Abbreviations: BMI, body mass index; DM, Diabetes; FBG, fasting blood glucose; FBI, fasting blood insulin; FFQ, Food frequency questionnaire; FPG, fasting plasma glucose; F/U, Follow-up HbA1C, Hemoglobin A1C; Homeostatic Model - Insulin Resistance HOMA-IR, ; HS, high school; HTN, hypertension; ITT, intent-to-treat; Med, Mediterranean; mo, month(s); N/A, Not applicable NR, not reported; NS, not statistically significant; Ob, Obesity; OW, Overweight; SEP/SES, Socioeconomic position/status; T2D, Type 2 Diabetes; TC, total cholesterol; TG, triglyceride; Tx, treatment; UPF, Ultra-processed food; WC, waist circumference; ∆, change; ♂ male; ♀ female

Table 11 Risk of bias for randomized controlled trials examining dietary patterns consumed by adults and older adults and risk of type 2 diabetes^a^

Article | Randomization | Deviations from intended interventions (effect of assignment) | Deviations from intended interventions (per-protocol) | Missing outcome data | Outcome measurement | Selection of the reported result | Overall
Babio, 2014 ^16^ | SOME CONCERNS | LOW | LOW | LOW | LOW | HIGH | HIGH
Bruno, 2020 ^17^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Calvo-Malvar, 2021 ^18^ | SOME CONCERNS | LOW | SOME CONCERNS | LOW | LOW | HIGH | HIGH
Georgoulis, 2020, 2021, and 2023^19–21^ | LOW | SOME CONCERNS | n/a | LOW | LOW | HIGH | HIGH
Gotfredsen, 2021 ^22^ | LOW | LOW | LOW | LOW | LOW | HIGH | HIGH
Howard, 2018 ^23^ | LOW | SOME CONCERNS | n/a | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS
Pavic, 2019 ^24^ | LOW | n/a | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Prentice, 2019 ^25^ | LOW | HIGH | n/a | SOME CONCERNS | HIGH | SOME CONCERNS | HIGH
Reidlinger, 2015 ^26^ | LOW | LOW | LOW | LOW | LOW | LOW | LOW
Salas-Salvado, 2014 ^27^ | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS
Sidahmed, 2014 ^28^ | LOW | LOW | LOW | LOW | LOW | HIGH | HIGH
Tussing-Humphreys, 2022 ^29^ | SOME CONCERNS | LOW | n/a | LOW | LOW | HIGH | HIGH

a Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (August 2019 version)” ( Sterne JAC, Savovic J, Page MJ . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366:14898.

Table 12 Evidence in adults and older adults from observational studies examining the relationship between dietary patterns and risk of type 2 diabetes^a^

Article Information | Intervention/exposure and comparator | Results | Methodological considerations
Ahmad, 2018^30^; USA; Women’s Health Study; Analytic N=25994; Participant characteristics:; - Health: BMI: 24.3 to 25, median; 25% HTN; 2% diabetes; 14% family history of MI; - Race and/or Ethnicity: NR; - SEP: NR, all health professionals; Selection data: All free of CVD at baseline; Excluded if missing biomarker data or FFQ | Age at Dietary Pattern: ≥45 y; [underlined: traditional Med Diet Score (tMED)] [Mitrou 2007 modified Fung 2005]:; Positive: Vegetables (not potatoes); Legumes; Fruit and Nuts; Grains; Fish; MUFA/SFA. Negative: Red and Processed Meat; Dairy Products.; Neutral: Alcohol; Methods: Index/Score | Follow-up: 12y; [underlined: Risk of T2D]: T2D’; tMED 0-3, HR: 1, ref; tMED 4-5, HR 0.79 95% CI: 0.69, 0.92;; tMED 6+, HR 0.72 95% CI: 0.61, 0.86,; p=0.002; Short-term T2D risk,; tMED 4-5, HR 0.79 95% CI: 0.68, 0.91;; tMED 6+, HR 0.75 95% CI: 0.63, 0.89,; p<0.001; 5-y T2D risk,; tMED4-5, HR 0.81 95% CI: 0.70, 0.94;; tMED 6+, HR 0.8 95% CI: 0.68, 0.95,; p=0.007; [underlined: HbA1C:] tMED 4-5 vs. 0-3 ref & HbA1c,; HR 0.77 95% CI: 0.67, 0.89;; tMED 6+ vs. 0-3 ref & HbA1c, HR 0.74 95% CI: 0.62, 0.88, p<.001; [underlined: HOMA-IR:] Lipoprotein IR score:; tMED 4-5 vs. 0-3 ref, HR 0.81 95% CI: 0.70, 0.94;; tMED 6+ vs. 0-3 ref, HR 0.79 95% CI: 0.67, 0.94, p=0.005; Summary: Inverse: Higher tMED & lower risk of T2D incidence, short-term and 5-y T2D risk, lower HbA1C, and lower lipoprotein IR | - Did not account for: SEP (all well-educated, health professionals); Race and/or ethnicity; Family history of diabetes; - Diet assessment: FFQ once (baseline); - Outcomes: Data NR, short-term and 5-y T2D risk based on scale of 0 to 100 (higher score= higher risk); - Indirect due to CVD as primary outcome of interest; - Funding: NIH
Ahmad, 2020^31^; USA; Women’s Health Study; Analytic N=25317; Participant characteristics:; - Health: Higher MED intake generally had better biomarker profiles, except for 9 biomakers that were similar across MED categories, including HbA1c, Blood pressure, LDL, TG, total cholesterol, lipoprotein (a), apolipoprotein B100, LDL particle concentration, TRL particle concentration and size etc.; - Race and/or Ethnicity: ‘predominantly’ White; - SEP: NR, all health professionals; Selection data: Excluded participants who had missing information on all the traditional and novel metabolic biomarkers and baseline diabetes | Age at Dietary Pattern: 52.9 y [9.9], mean; Mediterranean Diet Score (mMDS) [Trichopolou 2003; modified by Ahmad, 2018], Positive: Vegetables; Legumes; Fruit, Nuts; Cereals/Whole Grains; Fish; MUFA/SFA. Negative: Red and Processed Meat. Neutral: Alcohol; Methods: Index/Score | Follow-up: 19.8 [5.8] y mean [SD], T2D;; [underlined: Risk of T2D:] MED 0-3: HR 1, ref; MED 4-5: HR 1.08, 95% CI: 0.98, 1.19; MED ≥6: HR 0.91, 95% CI: 0.81, 1.03; P for trend=0.80; Summary: Null: MED &T2D | - Did not account for: SEP (all health professionals); Family history of diabetes; - Diet assessment: FFQ once (baseline); - Outcomes: Self report, may include T1D; - Significant association in ♀ with BMI≥25: MED 0-3, HR 1, ref; MED 4-5: HR 1.02, 95% CI: 0.92, 1.13; MED≥6: HR 0.84, 95% CI: 0.73, 0.96, P for trend=0.02; NS in ♀ with BMI<25: MED 4-5: HR 1.13, 95% CI: 0.89, 1.44; MED≥6: HR 1.12, 95% CI: 0.85, 1.49; P for trend=0.40. (both models without further adjusting BMI);; - Limited generalizibility of population; self-reported BMI, potential surveillance bias; - Funding: NIH; Swedish Heart-Lung Foundation and Henning och Johan Throne-Holst Stiftelse; Swedish Heart-Lung Foundation; NHLBI; NIDDK; AHA; Molino Family Trust; LabCorp
Alae-Carew, 2020^32^; Peru; CRONICAS; Analytic N=2313, T2D; Participant characteristics:; - Health: BMI ≥ 25 kg/m2: 67.3%; HTN: 25.4%; T2D: 8.3%; TV ≥ 2 h/d: 57.2%; Never smokers 56.6%; Moderate PA 55.2%; - Race and/or Ethnicity: NR; - SEP: Education: None 7.4%, Primary 38.4%, Secondary 32.7%, Further 21.6%; Currently Employed: Yes 64.5%, No 35.5%; SES: Lowest 32.1%, Middle 33.8%, Highest 34.2%; Selection data: Excluded some with HTN, T2D, high BMI, and all with pregnancy, active tuberculosis, physical disability, bedridden, unable to consent at baseline or LFU | Age at Dietary Pattern: ≥ 35 y; [underlined: ‘Stage 3’, ref:] Moderate refined grains; Moderate red meat; Moderate poultry; Low cooked vegetables; Moderate fruit; High seafood; Moderate potatoes; Moderate legumes; Low egg; Moderate UPF; High UPF; [underlined: ‘Stage 1’:] Low refined grains; Low dairy; No poultry; Low poultry; No green vegetables; No raw vegetables; High cooked vegetables; Low fruit; High potato; No legumes; Low egg; Low UPF; [underlined: ‘Stage 2’:] Low whole grains; Low refined grains; Low dairy; Low red meat; Low poultry; Low green vegetables; Low raw vegetables; Moderate cooked vegetables; Low fruit; High potato; Low legumes; Low egg; Low UPF; [underlined: ‘Stage 4’:] Moderate refined grains; High dairy; High red meat; Moderate red meat; High poultry; High green vegetables; Moderate raw vegetables; Moderate cooked vegetables; High fruit; Moderate legumes; High UPF; Methods: Latent Class Analysis | Follow-up: 30mo; [underlined: Risk of T2D:]; Prevalence; Stage 3, PR: 1, ref; Stage 1, PR: 0.29, 95% CI: 0.09, 0.99; Stage 2, PR: 0.73, 95% CI: 0.53, 1.01; Stage 4, PR: 0.86, 95% CI: 0.67, 1.09; Incidence; Stage 3, IRR: 1, ref; Stage 1, IRR: 0.64, 95% CI: 0.22, 1.87; Stage 2, IRR: 1.00, 95% CI: 0.55, 1.80; Stage 4, IRR: 1.32, 95% CI: 0.84, 2.05; Summary: Inverse: Stage 1 v. Stage 3 & T2D prevalence Inverse, NS: Stage 2 or Stage 4 v. Stage 3 & T2D prevalence; Inverse, NS: Stage 1 v. Stage 3 & T2D incidence; Null: Stage 2 v. Stage 3 & T2D incidence; Positive, NS: Stage 4 v. Stage 3 & T2D incidence | - Did not account for: TEI; Family history of diabetes; - Diet assessment: FFQ once (baseline); - Outcomes: Combination of self-report of physican diagnosis or n FPG ≥ 126 mg/dl; - Ethnicity was accounted for but not adjusted due to its collinearity with other risk factors; - Funding: None
Alhazmi, 2014^33^; Australia; Australian Longitudinal Study on Women’s Health; Analytic N=8370; Participant characteristics:; - Health: Ob, BMI≥30 kg/m2: 13-20%; High-PA 18-34%; Most self-rated health as good (86-93%) and did not consume Alcohol (74-88%); Smoke ≥ 20/d: 3-18%; - Women with higher diet scores tended to have higher physical activity levels, better self-rated health indices, less likely to be obese and heavy smokers, more likely to consume less alcohol and to have higher energy intakes.; - Race and/or Ethnicity: NR (Australian); - SEP: No differences by ARFS; Higher DGI more likely to live in urban area:; - DGI, Q1 v. Q5; - Urban 32 v. 37%;; - University degree: 11 v. 21%; Selection data: Excluded nonrespondents who did not complete the third survey, withdrew from the study completely or could not be contacted; ♀ who reported a daily energy intake <3347 kJ or >25104 kJ or who had a history of diabetes | Age at Dietary Pattern: 45 to 50 y; [underlined: Australian Recommended Food Behavior Score (ARFS)] [Collins, 2008]; Positive: Vegetables; Fruit; Grains; Protein foods (Nuts, Beans, Soy, Egg; Fish); Dairy (Reduced-fat/Skim milk; Low-fat cheese). Negative: Meat. Neutral: Fats (PUFA, MUFA, Non-Fat); Alcohol; modified Dietary Guideline Index (mDGI) [McNaughton, 2008], Postive: Vegetables; Fruits; Legumes; Cereals (breads, rice, pasta, and noodles); Whole Grain Cereals; Lean Meat/Meat alternatives (including fish); Total Dairy; Negative: SFA; Total fat; Added Sugars; Extra foods; Neutral: Alcohol (excluded salt and fluid components); Methods: Index/Score | Follow-up: 6 y mean, T2D; disease status every 3 years; [underlined: Risk of T2D:]; ARFS, Q1: OR 1, ref; Q2: OR 1.39, 95% CI: 0.96, 2.02; Q3: OR 1.41, 95% CI: 0.96, 2.06; Q4: OR 1.03, 95% CI: 0.72, 1.47; Q5: OR 0.99, 95% CI: 0.68, 1.43; p-trend=0.42; DGI, Q1: OR 1, ref; Q2: OR 0.79, 95% CI: 0.56, 1.11; Q3: OR 0.80, 95% CI: 0.57, 1.25; Q4: OR 0.71, 95% CI: 0.49, 1.03; p-trend=0.01; Summary: Inverse: DGI & T2D; Null: ARFS & T2D | - Did not account for: Race and/or ethnicity, Family history of T2D; - Diet assessment: FFQ once; - Outcomes: Self report, may include T1D (T1D differentiated in 3rd survey, not 4th or 5th); - Funding: Australian Government Department of Health and Ageing; the Ministry of Higher Education, Riyadh, Saudi Arabia
Allaire, 2020^34^; USA; Diabetes Prevention Program (DPP); Analytic N=2914; Participant characteristics:; - Health: 100% at high risk for diabetes (impaired glucose tolerance)and BMI ≥24; - Race and/or Ethnicity: 45% minority: 19% African American, 16% Hispanic, 5% American Indian, 4% Asian; - SEP: NR; Selection data: Included those with BMI ≥24 (≥22 in Asian Americans) & impaired glucose tolerance. Excluded those with diabetes at baseline; ever used antidiabetic medication other than during pregnancy; with medical conditions likely to limit life span and/or increase risk of intervention; CVD | Age at Dietary Pattern: 50.8y, mean (baseline ≥25 y); [underlined: Alternative HEI (AHEI)-2010] [Chiuve 2012], Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol; Methods: Index/Score | Follow-up: 3.2 y F/U, T2D; [underlined: Risk of T2D:]; All, HR: 0.980, 95% CI: 0.874, 1.098; Caucasian, HR: 0.899, 95% CI: 0.767, 1.055; African American, HR: 1.275, 95% CI: 0.981, 1.657; Hispanic, HR: 1.043, 95% CI: 0.788, 1.382; American Indian, HR: 0.662, 95% CI: 0.333, 1.317; Asian, HR: 1.422, 95% CI: 0.666, 3.034; between groups, p-trend=0.1391; Summary: Null: AHEI & incident T2D | - Did not account for: N/A (all accounted for); - Diet assessment: FFQ at baseline and 1y; - Outcomes: Fasted blood samples at mid-year visits and 2-h OGTT annual; T2D defined by 1997 ADA criteria as FPG ≥ 126 mg/dl (7 mmol/l) or 2-h post 75-g glucose load ≥ 200 mg/dl (11.1mmol/l) or use of anti-DM meds; Fasted blood samples at mid-year visits and 2-h OGTT; - AHEI change associated with Wt loss in Caucasian [−1.13 kg (0.19,p < 0.001)], Hispanic [-0.85 kg (0.29, p = 0.003)] and American Indian (−0.90, p = 0.156) participants. Effect sizes for African American (−0.36, p = 0.216) and Asian (0.49, p = 0.286) participants were small/NS. No difference in incident T2D by R/E; Secondary analysis reported results by lifestyle vs. metformin vs. placebo arms; no adjustment for multiple testing; Increases in AHEI over 1 year were largely driven by participants consuming less sodium, fewer trans fats, and fewer sugar-sweetened beverage; - Funding: NIH
Andre, 2020^35^; United Kingdom; BIOBANK; Analytic N=21,585; Participant characteristics:; - Health: Baseline differences in number of meds (p<0.0001) and comorbidities (p<0.0001) between those who did vs. did not develop T2D; - Race and/or Ethnicity: NR; - SEP: Baseline education level (college or university) differed between those who did vs. did not develop T2D (p<0.0001): 51% vs. 39% college or university; Selection data: Included those with data from at least 1 follow-up & w/out withdrawal of consent. Excluded those w/out diabetes status at baseline or at least 1 follow-up; with prevalent diabetes; ♀ w/ GDM; with diabetes at time 1 but not at time 2; without nutritional data; with nutritional data not reflecting usual diet | Age at Dietary Pattern: 56.5y, mean 40 to 69 y at baseline; [underlined: literature Mediterranean Diet Score (LitMDS)] [Sofi 2014], Positive: Vegetables; Legumes; Fruit and Nuts; Cereals; Fish; Olive Oil. Negative: Meat; Dairy Products. Neutral: Alcohol; Methods: Index/Score | Follow-up: 6.1y, mean; Risk of T2D: Direct effect (LitMDS → T2D); HR: 0.96, 95% CI: 0.93, 0.99; p-trend=0.0197; Indirect effect (LitMDS→ T2D mediated by overweight); HR: 0.90, 95% CI: 0.87, 0.92; p-trend<0.0001; Total effect (LitMDS → Overweight → T2D); HR: 0.86, 95% CI: 0.82, 0.90; p-trend<0.0001; Summary: Inverse: litMDS & T2D [direct (4% reduced risk) & total effect (14% reduced risk)] | - Did not account for: Age; Race and/or ethnicity; Anthropometry; Family history of diabetes; - Diet assessment: 24-hr recalls, five times (DP based on average of 2.2 surveys); - Outcomes: Self-report, may include T1D; - 10% of total effect of litMDS & T2D was mediated by reduced overweight per additional point of Medi diet score; Missing data (<3%) accounted for via imputation;; - Funding: Joint Programming Initiative, Healthy Diet for Healthy Life; French National Research Agency; Research Council for Biotechnology and Biological Sciences (UK); Ministry of Economy and Competitiveness (Spain)
Bantle, 2016^36^; USA; CARDIA; Analytic N=3358; Participant characteristics:; - Health: BMI 24.4 kg/m2 mean; Weight: 156.2 lbs, mean; - Race and/or Ethnicity at F/U Y25:; - T2D/Prediabetes: Black 36%, White 64%;; - Prediabetes: Black 54%, White 46%;; - T2D: Black 69%, White 31%; - SEP: NR; Selection data: Included data from Y0 and Y25. Excluded participants who had diabetes or prediabetes at Y0, no fitness or dietary intake data at Y0, unknown diabetes status at Y25. | Age at Dietary Pattern: 18 to 30 y; [underlined: “Americanized” Mediterranean Diet Score (AmMed Diet)] [Bantle 2016, modified Stefan, 2014], Positive: Vegetables; Legumes; Fruit and Nuts; Whole Grains; Fish and Seafood; Eggs; Milk; MUFA+PUFA/SFA. Negative: Red and Procesed Meat; Dairy Products; Sugar-sweetened and diet beverages; Refined Grains; Snack foods; Potatoes. Netural: Alcohol; Methods: Index/Score | Follow-up: 25 y, T2D; [underlined: Risk of T2D:] Per SD, OR: 0.90, 95%; CI: 0.79, 1.03, P=0.13; [underlined: Prediabetes:] Per SD, OR: 1.00, 95%; CI: 0.92, 1.08, P=0.96; Summary: Null: AmMedDiet & Pre-T2D, T2D | - Did not account for: Family history of diabetes; - Diet assessment: Diet assessed once at baseline using diet history questionnaire for CARDIA/this study; - Outcomes: Fasted/non-fasted blood measured via “standard protocols”; T2D from measures or self-report of diabetes-meds; - Funding: NHLBI; University of Alabama at Birmingham; University of Minnesota; Kaiser Foundation Research Institute; Johns Hopkins University School of Medicine; NIA; NIH
Bao, 2016^37^; USA; Diabetes & Women’s Health study; Nurses’ Health Study II Analytic N=4502; Participant characteristics:; - Health: BMI, kg/m2: 25.4 (5.5) to 29.1 (6.9); Family history of diabetes: 25% to 33%; Current smoking: 7.5% to 15%; PA, MET h/week: 15.4 (19.1) to 19.2 (23.1); - Race and/or Ethnicity: 90-95% White; - SEP: NR; Selection data: Included ♀ who reported GDM before 1991 or incident GDM through 2001. Excluded participants who reported chronic disease including T2D, CVD, cancer before GDM pregnancy or before the return of their first post-GDM FFQ, had a multiple-birth pregnancy, or did not return any post-GDM FFQ | Age at Dietary Pattern: 24 to 44 y; [underlined: Low-carbohydrate diets (LCD) score [Halton, 2006] (Q5 v. Q1]): Lower intakes of Vegetables; Fruits; Whole grains; Sugar-sweetened beverages and Higher Red meat [Similar poultry; fish; eggs; nuts]; intake data NR for animal- or plant-based LCD; Methods: Index/Score | Follow-up: up to 20 y, T2D; [underlined: Risk of T2D]:; LCD score, Q1, HR: 1, ref; Q2, HR: 0.95, 95% CI: 0.70, 1.30; Q3, HR: 1.02, 95% CI: 0.77, 1.36; Q4, HR: 1.28, 95% CI: 0.96, 1.71; Q5, HR: 1.36, 95% CI: 1.04, 1.78; p-trend=0.003; Animal LCD score, Q1, HR: 1, ref; Q2, HR: 0.97, 95% CI: 0.71, 1.32; Q3, HR: 1.12, 95% CI: 0.84, 1.50; Q4, HR: 1.18, 95% CI: 0.88, 1.58; Q5, HR: 1.40, 95% CI: 1.06, 1.84; p-trend=0.004; Vegetable LCD score, Q1, HR: 1, ref; Q2, HR: 1.38, 95% CI: 1.05, 1.81; Q3, HR: 1.24, 95% CI: 0.94, 1.63; Q4, HR: 1.14, 95% CI: 0.86, 1.51; Q5, HR: 1.19, 95% CI: 0.91, 1.55; p-trend=0.50; Summary: Positive: Overall LCD, animal LCD & T2D Null: Vegetable LCD & T2D | - Did not account for: Family history of diabetes; - Diet assessment: Diet assessed every 4y via FFQ; - Outcomes: Self-reported physician diagnosis, confirmed with self-report; T2D defined by ADA criteria as FPG ≥ 7 mmol/l, random PG (or no symptoms + OGTT) ≥ 11.1mmol/l, a/o use of anti-diabetes meds; sub-study validated; - Potential misclassification of dietary intakes, screening bias, limited generalizibility; - Funding: Eunice Kennedy Shriver National Institute of Child Health and Human Development, NIH; NIH; American Diabetes Association
Beigrezaei, 2023^38^; Iran; YaHS-TAMYZ; Shahedieh; Analytic N=8667; Participant characteristics:; - Health: Majority OW/Ob with mean BMI 25-29.9, 40%; 30-34.9, 22%, 35+ 8%; Majority never smokers (~12% current; 83% never); - Race and/or Ethnicity: NR (Iranian); - SEP: Education: 19-25% none; ~42% elementary; 19-24% highschool; 13-16% BS degree +; Marital status: ~92-93% married; Selection data: Excluded those: with implausible/incomplete dietary intake data; previous T1D or T2D; without response data or national identifier code; and/or who died | Age at Dietary Pattern: 20 to 60+y; (~6% 20-29; 26% 30-39; 32% 40-49; 22% 50-59; 13% 60+); [underlined: PCA -DP1]: Positive: processed meats, organ meats, fish, margarine, fruit juice, pizza, snacks, sweet dessert, and soft drinks. Negative: whole grains; [underlined: PCA-DP2]: Positive: dairy products, fruits, tomatoes, other vegetables, potatoes, refned grains, and vegetable oils; [underlined: PCA-DP3]: Positive: tea, mayonnaise, nuts, hydrogenated fats, sugars, and sof drinks; [underlined: PLS-DP1]: Positive: whole grains. Negative: processed meats, organ meats, poultry, fish, margarine, fruit juice, pizza, snacks, and sweet dessert; [underlined: PLS-DP2]: Negative: tea, potatoes, refned grains, sugars, and vegetable oils; [underlined: PLS-DP3]: Positive: fruits, tomatoes, other vegetables, and yoghurt drink. Negative: margarine; [underlined: DP1 -RRR:] Positive: whole grains. Negative: processed meats, red meats, poultry, fsh, margarine, fruit juice, pizza, snacks, sweet dessert, and sof drinks; [underlined: DP2-RRR]: Positive: poultry, fruits, sof drinks, and yoghurt drink. Negative: potatoes, refined grains, and mayonnaise; [underlined: DP3-RRR]: Positive: fruits, fruit juice, refined grains, and vegetable oils. Negative: processed meats, organmeats, margarine, and hydrogenated fats; Methods: Factor or cluster analysis:; PCA and RRR | Follow-up: 4-6 y (TaHS-TAMYZ 6 y; Shahedieh 6y); [underlined: Risk of T2D]:; PLS-DP2 & T2D, Q3 vs Q1, RR: 0.613, 95% CI: 0.39, 0.95, P-trend: 0.975; DP2-RRR & T2D, Q3 vs Q1, RR: 0.564, 95% CI: 0.36, 0.87, P-trend: 0.786; DP3-RRR & T2D, Q5 vs Q1, RR: 0.540, 95% CI: 0.33, 0.87, P-trend: 0.020; data NR for PCA-DP1, PCA-DP2, PCA-DP3, PLS-DP3, DP1RRR or PLS-DP1 & T2D (all NS); Summary: Null: PCA-DP1, 2, 3 & T2D; Null: PLS-DP1, 3 & T2D; Null: DP1-RRR & T2D; Inverse (Q1 vs. Q3 only): PLS-DP2,; DP2-RRR & T2D; Inverse (Q1 vs. Q5): DP3-RRR & T2D | - Did not account for: Race and/or ethnicity, alcohol, family history of diabetes; - Diet assessment: FFQ once (baseline); - Outcomes: Fasted (8-12h) blood samples collected in both cohorts; T2D based on registry linkage in YaHS-TAMYZ and phone call in Shahedieh; - Data not reported for results from multiple dietary patterns; - Identified 245 cases; Alcohol intake NR (presume due to religious/cultural factors); - Funding: Shahid Sadoughi University of Medical Sciences
Boonpor, 2022^39^; United Kingdom; BIOBANK 37 to 73y; Analytic N=203,790; Participant characteristics:; - Health: Mean BMI ~25-28, WC ~12.5cm; Most (41-64%) never smoked; - Race and/or Ethnicity: ~83% White; - ○ Vegetarians: 83.3% White; 15.1% South Asian; 0.3% Black; 0.1% Chinese; 1.2% mixed; - ○ Fish eaters: 94.8% White; 2.9% South Asian; 0.9% Black; 0.1% Chinese; 1.2% mixed; - ○ Fish & poultry eaters: 92.7% White; 4.0% South Asian; 1.4% Black; 0.1% Chinese; 1.; - SEP: Townsend Deprivation Index: low 26.8-34.9%, middle 32.735.2%, high (most deprived) 30.7-40.5%; Selection data: Excluded vegans; those with missing dietary data, no linked pimary care data to ascertain T2D; prevalent diabetes at baseline or within first 2 y F/U | Age at Dietary Pattern: 55y, mean; 37 to 73y; [underlined: Vegetarians:] consumption of cheese, milk, but not fish, poultry or red meat; [underlined: Fish eaters]: consumption of cheese, milk and fish but not poultry or red meat; [underlined: Fish & poultry eaters]: consumption of cheese, milk, fish and poultry, but not red meat; [underlined: Meat eaters]: consumption of cheese, milk, fish, poultry and red meat; [underlined: Varied]: reported that diets varied often; Methods: Other: Vegetarian | Follow-up: 5.4y, median; [underlined: Risk of T2D]: Multivariable + BMI; Fish & poultry eaters, HR: 0.82, 95%; CI: 0.59, 1.16, p-trend=0.264; Fish eaters, HR: 0.69, 95% CI: 0.51, 0.92, p-trend=0.013; Vegetarians, HR: 1.15, 95% CI: 0.90, 1.47, p-trend=0.27; Varied, HR: 1.06, 95% CI: 0.96, 1.16, p-trend=0.233; Summary: NS/Null: ‘Fish eater’, ‘Vegetarian’ , or ‘Varied DP (vs. ‘Meat eater’ DP) & T2D; Inverse: ‘Fish eater’ vs. ‘Meat eater’ DP & (lower) T2D | - Did not account for: Race/Ethnicity, Family history of diabetes, Other: TEI; - Diet assessment: FFQ once and a 24h in sub-set; - Outcomes: T2D based on linkage to medical records; - Similar results in model that controlled for WC rather than BMI; Excluded ‘Vegan’ group due to small sample size; Dietary patterns lack full description of all food groups conusmed; - Funding: Chilean Government PhD Scholarship Program; Royal Thai Government Scholarship
Brayner, 2021^40^; United Kingdom; BIOBANK; Analytic N=16523 (T2D; CVD; Ob); 14927 (WC); Participant characteristics:; - Health: Family history of diabetes, 9.5%; - Race and/or Ethnicity: 97.5% White; 2% Mixed; <1% Other; - SEP: Townsend Deprivation Index: low 41%, middle 34%, high (most deprived) 25%; Selection data: Excluded those with missing; exposure/outcome/covariate, <2 valid diet assessments; pregnancy; self-reproted T2D, CVD, Obesity, or Abdominal Obesity prior to baseline and at first F/U | Age at Dietary Pattern: 55y, mean; [underlined: ‘DP1’]: higher intake of nuts, seeds, and butter and lower intake of fruit and low-fat yogurt; ‘[underlined: DP2’]: higher intake of butter and high fat cheese and lower intake of nuts and seeds; Methods: RRR: Response variables were %E from SFAs, PUFAs, and MUFAs | Follow-up: 6.3y, mean; [underlined: Risk of T2D]:; DP1 T2, OR: 1.13, 95% CI: 0.82, 1.56;; DP1 T3, OR: 1.09, 95% CI: 0.78, 1.53;; p-trend=0.59; DP2 T2, OR: 1.02, 95% CI: 0.73, 1.41;; DP2 T3, OR: 1.01, 95% CI: 0.73, 1.40;; p-trend=0.96; Summary: Null: DP1 or DP2 & T2D incidence | - Did not account for: Race/Ethnicity; - Diet assessment: 24-h record/FFQ “hybrid” at baseline and every 6 months (≥3 nonconsecutive, validated, web-based); - Outcomes: Self-report in 2 of 3 F/U of physician diagnosis; May include T1D; - Funding: None
Cea-Soriano, 2021^41^; Spain; PREDAPS; Analytic N=1184; Participant characteristics:; - Health: 100% Prediabetes; 43% Ob; 67% abdominal Ob; 100% Prediabetes; 38% Family history of diabetes; 67% HTN; 79% HighLDL, 24% Low-HDL; 8% CVD; <3% kidney failure; 55% inactive; 14% heavy alcohol use; 17% current smoker; - Race and/or Ethnicity: NR (Spanish); - SEP: NR; Selection data: Included participants aged between 30 and 74 y whom consecutviely sought medical attention for any reason, and who had prediabetes, i.e., glucose impairment; Excluded participants who had diabetes, terminal disease, pregnancy, surgery or hospital admission in the previous three months at study entry, or any hemotologic disease that could alter | Age at Dietary Pattern: 30 to 74 y; [underlined: Adapted Mediterranean-based Diet Score (adMedDietScore)]; [Panagiotakos 2007], Positive: Vegetables; Potatoes; Legumes; Nuts; Fruit; Rice, pasta, bread; Fish; Veg. Oils. Negative: Meats; Cold Meats and Sausage; Dairy; Alcohol; Sweets [Cake]; Animal fat; Fried food; Ready meals; Preserved food and snacks; Methods: Index/Score | Follow-up: 4.2 y mean T2D; [underlined: Risk of T2D]: Multivariate adjusted, High v. Low/Medium: HR 0.67, 95% CI: 0.47, 0.98; Summary: Inverse: MedDietScore & T2D | - Did not account for: Race and/or ethnicity, SEP; - Diet assessment: FFQ once (baseline); - Outcomes: Fasted blood samples collected, HbA1C via HPLC and calcuated via IFCC; - Stratified analysis: among age<65y, age-specific propensity score HR 0.48, 95% CI: 0.27, 0.86; age≥65y, HR 0.80, 95% CI: 0.49, 1.32.; - Did not include prediabetes diagnosed based on impaired glucose tolerance;; - Funding: Sanofi and Novartis (French multinational pharmaceutical & healtcare company) HbA1c values.
Cespedes, 2016s^42^; USA; Women Health Initiative (WHI); Analytic N=101,504; Participant characteristics:; - Health: BMI: 26-28 kg/m2, mean; Family history of T2D, 27-31%; Current HRT 36-47%; Current smoker 3-12%; PA, mean (sd): 9 (12) to 19 (16) MET-hr/wk; Alcohol use, mean (sd): 0.36 (0.9) 0.49 (0.68)drinks/wk.; - Women with better-quality diets had lower BMI, and were more likely to be physical active, current users of hormone therapy and less likely to have a family history of T2D;; - Race and/or Ethnicity: nonHispanic white: ~85%; - SEP: College-educated: 41%; - Neighborhood SES (range 20 to 100), mean (sd) by aMED score SD <-1; −1 to 1; > 1: 75 (9); 76 (8); 78 (7); Selection data: Participants from the WHI Observational Study and the Calcium and Vitamin D and Hormone Therapy trials. Excluded ♀ in both arms of the WHI diabetes Trial due to the likelihood of dietary changes and the systematically higher (>32%) intake of energy from fat; ♀ with missing dietary intake data or missing information on prevalent diabetes at baseline; those with prevalent diabetes outside of pregnancy and implausible energy intakes (<600 or >5/k kcal/d) | Age at Dietary Pattern: 50 to 79 y; [underlined: Alternate Med Diet Score [Fung 2005]]; [underlined: aMED:] Positive: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA/SFA.; Negative: Red and Processed Meat. Neutral: Alcohol: Wine. [low to moderate dairy, fish, poultry]; [underlined: Healthy Eating Index [Guenther 2013] HEI-2010:] Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; Fatty Acids. Negative: Refined Grains; Added Sugars in “Empty Calories”; Solid Fats in “Empty Calories”; Sodium; [underlined: Alternative HEI [Chiuve 2012] AHEI-2010:] Positive: Vegetables (not potatoes, French fries); Fruit; Legumes; Whole Grains; Oily fish; PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol; [underlined: DASH score [Fung 2008]:] Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Sodium [low in sweets]; Methods: Index/Score | Follow-up: 15 y median, T2D; [underlined: Risk of T2D]: aMED:; Per-SD increase, HR: 0.95, 95% CI: 0.95, 0.97; Per 10% increase, HR: 0.97, 95% CI: 0.96, 0.98; Q1, HR: 1, ref; Q2, HR: 0.90, 95% CI: 0.85, 0.96; Q3, HR: 0.95, 95% CI: 0.90, 1.01; Q4, HR: 0.92, 95% CI: 0.87, 0.98; Q5, HR: 0.85, 95% CI: 0.80, 0.90; HEI-2010; Per-SD increase, HR: 0.93, 95% CI: 0.92, 0.95; Per 10% increase, HR: 0.94, 95% CI: 0.92, 0.96; Q1, HR: 1, ref; Q2, HR: 0.92, 95% CI: 0.87, 0.97; Q3, HR: 0.90, 95% CI: 0.85, 0.95; Q4, HR: 0.85, 95% CI: 0.80, 0.91; Q5, HR: 0.83, 95% CI: 0.78, 0.89; AHEI-2010; Per-SD increase, HR: 0.92, 95% CI: 0.90, 0.94; Per 10% increase, HR: 0.92, 95% CI: 0.90, 0.94; Q1, HR: 1, ref; Q2, HR: 0.93, 95% CI: 0.88, 0.99; Q3, HR: 0.87, 95% CI: 0.82, 0.92; Q4, HR: 0.84, 95% CI: 0.79, 0.90; Q5, HR: 0.78, 95% CI: 0.73, 0.83; DASH score; Per-SD increase, HR: 0.90, 95% CI, 0.89, 0.92; Per 10% increase, HR: 0.93, 95% CI, 0.92, 0.95; Q1, HR: 1, ref; Q2, HR: 0.87, 95% CI: 0.82, 0.92; Q3, HR: 0.83, 95% CI: 0.78, 0.88; Q4, HR: 0.77, 95% CI: 0.72, 0.82; Q5, HR: 0.74, 95% CI: 0.69, 0.80; Summary: Inverse: aMED, HEI-2010, AHEI-2010, DASH & T2D | - Did not account for: N/A; - Diet assessment: FFQ once (baseline); - Outcomes: Self-reported physician diagnosis, confirmed with self-report of anti-diabetes meds (accuracy validated for WHI); - Sensitivity analysis adding alternative and additional measures of adiposity, hypertension, geographic region, neighborhood socioeconomic status, or coffee intake to the models did not materially alter the results.; - Single diet assessed used; - Potential misclassification due to self-reported T2D; FFQ may not fully capture culturally specific foods; residual confounding; - Results examined by race/ethnicity demonstrated that inverse association between aMED & T2D was NS among black and Asian ♀; DASH score & T2D was NS among Asian ♀; - Funding: NIDDKD;NHLBI; FDA; Department of Veterans Affairs; NIH; Cystic Fibrosis Foundation;
Chen, 2018^(Diet)43^; Singapore; Singapore Chinese; Health Study; Analytic N=45,411; Participant characteristics:; - Health: BMI, kg/m2, mean: ~ 23.0; HTN: ~ 17 to 21%; Current smoker: ~8 to 33%; Current alcohol drinker: ~11 to 30%; High-PA: ~27 to 43%; - Race and/or Ethnicity: 100% Chinese in Singapore; Cantonese dialect, %:; - SEP: Higher education,%; - aMED Q1: 20.2% Q5: 42.3%; - AHEI-2010 Q1: 26.9% Q5: 39.8%; - DASH Q1: 26.8% Q5: 36.6%; - PDI Q1: 21.8% Q5: 39.3%; - hPDI Q1: 30.9%Q5: 32.5%; Selection data: Excluded participants who had known diabetes, CVD, or cancer at baseline; had unrealistic energy intake; or LFU/died before diagnosis of diabetes | Age at Dietary Pattern: 45 to 74 y; [underlined: Alternate Med Diet Score (aMED)]; [Fung 2005] Positive: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA/SFA.; Negative: Red and Processed Meat.; Neutral: Alcohol; [underlined: Alternative HEI (AHEI)-2010] [Chiuve 2012], Positive: Vegetables (not potatoes/French fries); Fruit; Legumes and Nuts; Whole Grains; Oily fish; PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Sodium. Neutral: Alcohol [excluded Trans FA]; [underlined: DASH score] [Fung 2008], Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Total (not just low-fat) Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Sodium; [underlined: Plant-Based Diet Index (PDI)] [Satija, 2016], Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Negative: Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; [underlined: Healthful PDI (hPDI)] [Satija, 2016], Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Negative: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; Methods: Index/Score | Follow-up: 11.1 y median, T2D; [underlined: Risk of T2D]:; aMED; Q1, HR: 1, ref; Q2, HR: 0.96, 95% CI: 0.88, 1.05; Q3, HR: 0.92, 95% CI: 0.84, 1.00; Q4, HR: 0.83, 95% CI: 0.76, 0.91; Q5, HR: 0.84, 95% CI: 0.77, 0.92; P-trend < 0.001; Per SD increment, HR: 0.93, 95% CI: 0.91, 0.96; AHEI-2010; Q1, HR: 1, ref; Q2, HR: 0.93, 95% CI: 0.86, 1.01; Q3, HR: 0.93, 95% CI: 0.86, 1.01; Q4, HR: 0.86, 95% CI: 0.79, 0.94; Q5, HR: 0.79, 95% CI: 0.73, 0.87; P-trend < 0.001; Per SD increment, HR: 0.93, 95% CI: 0.90, 0.95; DASH index; Q1, HR: 1, ref; Q2, HR: 0.95, 95% CI: 0.87, 1.03; Q3, HR: 0.87, 95% CI: 0.79, 0.96; Q4, HR: 0.83, 95% CI: 0.76, 0.91; Q5, HR: 0.71, 95% CI: 0.65, 0.79; P-trend< 0.001; Per SD increment, HR: 0.90, 95% CI: 0.87, 0.93; PDI; Q1, HR: 1, ref; Q2, HR: 0.96, 95% CI: 0.87, 1.05; Q3, HR: 0.92, 95% CI: 0.85, 1.01; Q4, HR: 0.87, 95% CI: 0.79, 0.95; Q5, HR: 0.83, 95% CI: 0.76, 0.92; P-trend < 0.001; Per SD increment, HR: 0.94, 95% CI: 0.92, 0.97; hPDI; Q1, HR: 1, ref; Q2, HR: 0.93, 95% CI: 0.85, 1.01; Q3, HR: 0.93, 95% CI: 0.85, 1.01; Q4, HR: 0.82, 95% CI: 0.75, 0.90; Q5, HR: 0.81, 95% CI: 0.75, 0.89; P-trend<0.001; Per SD increment, HR: 0.93, 95% CI: 0.90, 0.95; Summary: Inverse: aMED, AHEI2010, DASH, PDI, or hPDI & T2D | - Did not account for: Family history of diabetes; - Diet assessment: FFQ once (baseline); - Outcomes: Self-reported physician diagnosis by phone; incident T2D validated with hospital data linkage, antidiabetes Tx, or symptom report; - Sensitivity analyses by recontrcuting aMED and AHEI-2010, or excluding T2D cases within the first 4 years of followup yielded similar results; - Other limitations: Deviation of Dietary pattern scores from original version: trans-fat omitted from AHEI-2010; total dairy food rather than low-fat dairy food for DASH; potential misclassification of diabetes due to self-report; Inverse associations between each DP & T2D were mostly similar in never smokers and former smokers (associations were n/s for PDI and hPDI in former smokers); NS in lighter smokers (1–12 cigarettes/day) or heavier smokers (≥13 cigarettes/day); - Funding: NIH; National Medical Research Council, Singapore; China Scholarship Council
Chen, 2018 ^(Plant)44^; Netherlands; Rotterdam Study Analytic N=6798 total; Insulin resistance: 6514; PreT2D: 5768; T2D: 6770; Participant characteristics:; - Health: BMI, kg/m2. mean: 26.6 ± 3.9; - Family history of diabetes: 10.8%; HTN: 42.3%; HC: 45.4%; Current smoking: 22.7%; - Physical activity, 58.4 ± 55.8 METhr/wk; Current food supplement use: 16.5%; - Race and/or Ethnicity: NR (Dutch); - SEP: Education level, %; - ○ Primary: 11.8%; - ○ Lower: 40.9%; - ○ Intermediate: 29.0%; - ○ Higher: 18.3%; Selection data: Excluded those with: non-valid/unreliable/extreme dietary intake according to a trained nutritionist at baseline; missing diabetes data at F/U, prediabetes data or HOMA-IR data for respective analyses; or who had T2D or Prediabetes at baseline | Age at Dietary Pattern: 62.0 [7.8] y, mean (enrolled ≥45+ y); [underlined: Plant-based dietary index, adapted (aPDI)] [Martinez-Gonzalez 2014; Satija, 2016], Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Alcoholic drinks; Negative: Yogurt, lowfat; Yogurt, high-fat; Animal fats; Milk, lowfat; Milk, whole fat; Cheese; Eggs, Fish/seafood; Unprocessed lean mea (poultry); Processed and red meat; Dairy-desserts; Methods: Index/Score | Follow-up: 5.7 y median, preT2D 7.3 y median, T2D; [underlined: Risk of T2D]: aPDI, HR: 0.87, 95% CI: 0.79, 0.99; P-trend<0.05; [underlined: Prediabetes]: aPDI, HR: 0.93, 95% CI: 0.85, 1.03; p-trend NS; [underlined: HOMA-IR:] aPDI, β = −0.05, 95% CI: 0.06, −0.04; p-trend<0.001; Summary: Inverse: PDI & HOMA-IR, T2D; NS, Inverse: PDI & Prediabetes | - Did not account for: Race and/or ethnicity; - Diet assessment: FFQ once (baseline); - Outcomes: Fasted blood samples collected; HOMA-IR calculated as FPG (mmol/l) x FBI (mU/l)/22.5; - Sensitivity analyses by controlling dietary guidelines score, additionally adjusting HTN and hypercholesterolemia, excluding participants with chronic diseases at baseline did not show substantially different results; excluding participants who developed T2D or preT2D in the first 2 y F/U modestly attenuated the association.; - Funding: Erasmus University Medical Center and Erasmus University Rotterdam; The Netherlands Organization for Health Research and Development; the Research Institute for Diseases in the Elderly; The Netherlands Genomics Initiative; the Ministry fo Education, Culture and Science; the Ministry of Health, Welfare and Sports; the European Commission, the Municipality of Rotterdam.
Chen, 2021^45^; USA; HPFS/NHS; Analytic N=192,567 (NHS: 76,530;; NHS II: 81,569; HPFS: 34,468); Participant characteristics:; - Health: Family history of diabetes: 25-35%; HTN: 8.5-32%; HC: 20- 46%; Current smoker: 8-19%; - Race and/or Ethnicity: >90% White; - SEP: NR, all health professionals; Selection data: Excluded those with diabetes, cancer, or CVD and those who died before baseline of this analysis; those without follow-up dietary data or who did not complete two consecutive FFQs; those who reported implausible calorie intakes | Age at Dietary Pattern: 25 to 75 y at baseline (NHS: 30-55y; NHS II: 2542y; HPFS: 40-75y); [underlined: Plant-Based Diet Index (PDI) [Satija, 2016]:] Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Negative: Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods (excluded alcohol and margarine); [underlined: healthful PDI (hPDI)]: Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Negative: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods (excluded alcohol and margarine); [underlined: unhealthful PDI (uPDI)]: Negative: Whole grains; Fruits; Vegetables; Nuts; Legumes; Vegetable oils; Tea/coffee; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; Positive: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts (excluded alcohol and margarine); Methods: Index/Score | Follow-up: 22 y (NHS); 27 y (NHS II); 26 y (HPFS); [underlined: Risk of T2D]: Incident T2D- ΔPDI; Large ↓, HR: 1.12, 95% CI: 1.05, 1.20; Small ↓, HR: 1.05, 95% CI: 1.00, 1.11; No change, HR: 1.00 , ref; Small ↑, HR: 0.93, 95% CI: 0.89, 0.98; Large ↑, HR: 0.91, 95% CI: 0.86, 0.97; p-trend<0.0001; per 10% ↑, HR: 0.93, 95% CI: 0.91, 0.95; Incident T2D- ΔhPDI; Large ↓, HR: 1.23, 95% CI: 1.16, 1.31; Small ↓, HR: 1.11 95% CI: 1.05, 1.16; No change, HR: 1.00, ref; Small ↑, HR: 0.97, 95% CI: 0.92, 1.02; Large ↑, HR: 0.97, 95% CI: 0.85, 1.10; p-trend=0.002 per 10% ↑, HR: 0.91, 95% CI: 0.87, 0.95; Incident T2D- ΔuPDI; Large ↓, HR: 1.03, 95% CI: 0.92, 1.17; Small ↓, HR: 1.07, 95% CI: 0.98, 1.16; No change, HR: 1.00 , ref; Small ↑, HR: 1.02, 95% CI: 0.97, 1.07; Large ↑, HR: 1.06, 95% CI: 0.99, 1.13; p-trend=0.78; per 10% ↑, HR: 0.99, 95% CI: 0.94, 1.05; Summary: Null: ΔuPDI & incident T2D; Inverse: ΔPDI, ΔhPDI & incident T2D | - Did not account for: SEP; - Diet assessment: Diet assessed every 4y via FFQ, outcomes collected every 2 y; - Outcomes: Self-reported physician diagnosis, confirmed with self-report; Incident T2D defined by FPG ≥ 7 mmol/l (7.8 if <1998), random PG (or no symptoms + OGTT) ≥ 11.1mmol/l, a/o use of antidiabetic agents; sub-study validated; Funding: NIH
Choi, 2020^46^; USA; CARDIA; Analytic N=2534; Participant characteristics:; - Health: BMI, kg/m2: 23.1 ± 4.5 to 25.2 ± 5.6; Parental history of diabetes: 18 to 32%; - WC: 75-80 cm; Weight: 66.4±13.2 to 74.1±17.1 kg; PA: 344-486 units; Current smoker: 17-34%; Alcohol use, drinks/d, Y0: 0.64 ± 1.28 to 1.08 ± 1.68; - Race and/or Ethnicity: 31.8-37.4% White < median vs. 72.2-83.7% White ≥ median Y0-20 APDQS; - SEP: Highest grade of education, years:; - ○ < median Y0 APDQS, 20-y change in APDQS Q1: 14.7 ± 2.6; Q3: 15 ± 2.6; Q5: 15.7 ± 2.6; - ○ ≥ median Y0 APDQS, 20-y change in APDQS Q1: 16.5 ± 2.4; Q3: 16.8 ± 2.4; Q5: 17 ± 2.3; Selection data: Recruited black and white men and ♀ aged 18-30 years from communities at 4 U.S. cities who attended CARDIA at Y20 Excluded participants who did not complete dietary history at Y0 and Y20; had an implausible energy intake; did not provide information regarding smoking status at Y0 or physical activity at Y0 or Y20. Excluded participants who had diabetes in Y0-Y20 or were not examined at Y25 or Y30 for these analyses. | Age at Dietary Pattern: 18 to 30 y; [underlined: A Priori Diet Quality Score, APDQS]; [Sjitmsa, 2012], plant-centered focus, Positive: Vegetables; Legumes; Fruit; Nuts, Seeds; Whole Grains; Fish; Low-Fat Dairy; Vegetable Oil; Beer, Wine, Liquor; Tea, Coffee; Negative: Fried potatoes; High-fat meat; High-Fat Dairy; Desserts; Sugar-sweetened soft drinks; Butter; Fried Foods; Salty Snacks; Neutral: Potatoes; Fruit Juices; Refined grains; Eggs; Shellfish; Lean meat; Margarine; Chocolate & Diet Soft Drinks; Methods: Index/Score | Follow-up: 9.3 [1.7] y mean, T2D; [underlined: Risk of T2D]: 20-year change APDQS predicting Y20-Y30 T2D; Q1: HR 1.30, 95% CI: 0.84, 2.01; Q2: HR 1, ref; Q3: HR 1.02, 95% CI: 0.66, 1.55; Q4: HR 0.90, 95% CI: 0.58, 1.40; Q5: HR 0.52, 95% CI: 0.31, 0.85; Each 1-SD increment: HR 0.71, 95%; CI: 0.59, 0.86; P for trend<0.001; Y0 APDQS predicting Y20-Y30 T2D; Q1: HR 1, ref; Q2: HR 0.59, 95% CI: 0.40, 0.88; Q3: HR 0.53, 95% CI: 0.35, 0.81; Q4: HR 0.41, 95% CI: 0.25, 0.66; Q5: HR 0.31, 95% CI: 0.17, 0.58; Each 1-SD increment: HR 0.63, 95%; CI: 0.51, 0.78; P for trend<0.001; Y20 APDQS predicting Y20-Y30 T2D; Q1: HR 1, ref; Q2: HR 0.97, 95% CI: 0.69, 1.38; Q3: HR 0.59, 95% CI: 0.38, 0.91; Q4: HR 0.57, 95% CI: 0.35, 0.93; Q5: HR 0.33, 95% CI: 0.18, 0.61; Each 1-SD increment: HR 0.68, 95%; CI: 0.57, 0.80; P fro trend<0.001; Summary: Inverse: APDQS 20-year change, Y0, Y20 & T2D incidence from Y20 to Y30 | - Did not account for: N/A; - Diet assessment: Diet history at year 0, 7, and 20 (validated; change assessed); - Outcomes: Self-reported use of anti-diabetic meds, FBG ≥ 126 mg/dl, 2h-OGTT ≥ 200 mg/dL and/or HbA1C ≥ 6.5% (48 mmol/L) defined incident T2D at Y25 or Y30; - Similar but weaker inverse association as the 20-year change was observed for 7-year change in APDQS in relation to risk of diabetes in the subsequent 23-year period; results for 7-year change and change in BMI, WC and Wt were similar to 20-year change as well.; - There was no interaction between APQDS change and age, race, sex and education.; - Change in diet quality may not have been fully captured using only two time points, Y0 and Y20.; - Funding: NHLBI; the Healthy Food, Healthy Lives Institute and the MnDRIVE Global Food Ventures Professional Development Program, University of Minnesota Twin Cities
Choi, 2023^47^; USA; CARDIA; Analytic N=4547; Participant characteristics:; - Health: CVH health score 9.2-11.1 (highest in no- group); - Parental history of diabetes: 24.4% in No diabetes group; 53.5% in early onset diabetes group; 41.8% in later-onset diabetes group; - Race and/or Ethnicity: 49% Black; 51% White (No diabetes 46.7% Black; early onset diabetes 66.4% Black; later-onset diabetes 64.1% Black); - SEP: Maximum educational attainment: 15.5y no diabetes; 14.7y early-onset diabetes; 15.1y later-onset diabetes; Selection data: Excluded those with hisotry of diabetes at or before baseline; pregnancy; lacked data on diabetes; never attended F/U; lacked Y0 information on any cardiovascular health components; withdrew consent | Age at Dietary Pattern: 24y, mean; 18 to 30 y at baseline; [underlined: a priori diet quality score, APDQS] [Sjitmsa, 2012]: Positive: Vegetables-Green; Vegetables-Yellow; Vegetables-Other; Tomatoes; Beans/Legumes; Fruit; Avocado; Nuts and Seeds; Soy Products; Whole Grains; Fish, fatty not fried; Fish, lean not fried; Poultry; Low-Fat Dairy; Beer, Wine, Liquor; Tea, Coffee. Negative: Fried potatoes; High-fat meat; Processed meat; Organ meat; Fried Fish; Fried Poultry; Whole-Fat Dairy; Butter; Soft drinks; Grain Desserts; Pastries; Sweets; Salty Snacks; Sauces. Neutral: Potatoes; Lean red meats; Fruit Juices; Refined grains; Eggs; Shellfish; Margarine; Chocolate; Diet Soft Drinks; Meal replacements; Pickled foods; Soups, Sugar substitutes; Methods: Index/Score | Follow-up: 30y; [underlined: Risk of T2D]: Early onset v. no diabetes; T1, OR: 1.52, 95% CI: 0.85, 2.72; T2, OR: 1.34, 95% CI: 0.77, 2.33; T3, OR: 1, ref; Late onset v. no diabetes; T1, OR: 1.38, 95% CI: 1.05, 1.83; T2, OR: 1.26, 95% CI: 0.98, 1.62; T3, OR: 1, ref; Summary: Inverse: APDQS & lateonset diabetes; NS/Null: APDQS & early onset diabetes | - Did not account for: Physical activity, Anthropometry, or Smoking in APDQS analysis as co-exposures; - Diet assessment: one diet history; - Outcomes: Fasted (8h+) blood samples collected; T2D cases FBG ≥ 126 mg/dL; 2-h OGTT 75g ≥ 200 mg/dL; HbA1C ≥ 6.5%, or reported Tx with antidiabetes meds (verified med at clinic); may include T1D; - Physical activity, anthropometry (BMI), and smoking evaluated as components of Cardiovascular Health score & separately as individual predictors. Smoking & early/late onset diabetes NS. Physical activity & early/late onset diabetes NS. BMI & early/late onset diabetes postively associated.; - Funding: NHLBI; University of Alabama at Birmingham; University of Minnesota; Kaiser Foundation Research Institute
Conway, 2018 ^48^; USA; Southern Community Cohort Study; Analytic N=38,064 total: 24000 black, 14064 white in primary analyses, from entry to 1st F/U; Participant characteristics:; - Health, among blacks, whites:; - ○ BMI 25-29.9 kg/m2: 30.9%, 33.5%;; - ○ BMI 30-34.9: 22.8%, 20.5%;; - ○ BMI 35-39.9: 12.3%, 8.7%;; - ○ BMI≥40: 10.4%, 6.8%; - ○ HTN: 53.4%, 42.4%;; - ○ Current smoking: 38.8%, 30.6%;; - ○ PA: 19-33% MET-h; - Race and/or Ethnicity: Black: 63%; White: 38%; - SEP: Education: < HS: 22.3%; HS/vocational: 37.9%; ≥HS: 39.8%; - Income: < $15K: 46.5%; $15K- $24999: 21.1%; ≥$25K: 32.4%; - Insurance coverage: None: 35.4%; Medicaid/Medicare: 30.4%; Other: 34.2%; Selection data: Restricted to cohort members who completed 1^st^ F/U and did not report diabetes at entry for incident T2D cases, and restricted cases to self-reported T2D on antidiabetic meds; Or participants who did not report diabetes ever and restriced cases to T2D as those on meds at F/U; Excluded few participants with missing data on covariates | Age at Dietary Pattern: 40 to 79 y; [underlined: Healthy Eating Index (HEI-2010]); [Guenther 2013], Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; Fatty Acids. Negative: Refined Grains; Added Sugars in “Empty Calories”; Solid Fats in “Empty Calories”; Sodium; Methods: Index/Score | Follow-up: ~ 7.5y total (1st F/U: 4.5 y median (1 to 10 y), 2nd F/U: 3y median after 1st); [underlined: Risk of T2D]: Among Black; Q1, OR: 1, ref; Q2, OR: 1.06, 95% CI: 0.93, 1.20; Q3, OR: 1.00, 95% CI: 0.88, 1.14; Q4, OR: 0.94, 95% CI: 0.82, 1.08; P-trend=0.37; Among White; Q1, OR: 1, ref; Q2, OR: 1.00, 95% CI: 0.81, 1.24; Q3, OR: 1.08, 95% CI: 0.86, 1.35; Q4, OR: 0.95, 95% CI: 0.74, 1.22; P-trend=0.78; Second Follow-up:; Among Black; Q1, OR: 1, ref; Q2, OR: 1.09, 95% CI: 0.91, 1.29; Q3, OR: 0.91, 95% CI: 0.75, 1.09; Q4, OR: 0.86, 95% CI: 0.71, 1.06; P-trend=0.08; Among White; Q1, OR: 1, ref; Q2, OR: 0.98, 95% CI: 0.75, 1.29; Q3, OR: 0.87, 95% CI: 0.65, 1.16; Q4, OR: 0.69, 95% CI: 0.49, 0.96; P-trend=0.12; Summary: Inverse, NS: Higher HEI-10 & Lower T2D | - Did not account for: Alcohol, Physical activity (analyzed), Smoking (analyzed), Family history of diabetes, Other: TEI; - Diet assessment: FFQ once; - Outcomes: Self-reported physician diagnosis, confirmed with self-report of anti-diabetes meds (accuracy validated); - Secondary/Sensitivity analyses classifying all people self-reporting diabetes as cases generated similar results.; - Funding: NIH; NCI; NIDDKD
den Braver, 2019; Netherlands; The Hoorn Study + The; New Hoorn Study; Analytic N=2951, T2D; 2629, pre-T2D; 1603, FPG; Participant characteristics:; - Health: BMI, kg/m2: 26.1 (3.5) mean; HTN, N (%): 1015 (34.4%); - FBG, mmol/L: 5.4 ± 0.5; - Current smoking, N (%): 676 (22.9%); - Cigarette years: 230.2 ± 497.4; - Moderate PA min/wk: 7.0 ± 8.2; - TG, mmol/L: 1.2 ± 0.8; Alcohol, g/d: 7.3 ± 14.9; - Race and/or Ethnicity: White, ‘predominantly’; - SEP: Education Low: 14%; Middle 58%; High 27%; Selection data: Excluded participants with preT2D based on FPG, 2-h glucose and HbA1c, and T2D based on blood parameters, physician diagnosis and medication use, at baseline for the analyses with outcome preT2D, and T2D at baseline for analyses with outcome T2D; extreme/missing dietary intake or missing data on preT2D/T2D at baseline or F/U | Age at Dietary Pattern: 56.5 [7.5] (40 to 65) y, at baseline; [underlined: Dutch Healthy Diet Index 2015 (DHD][underlined: 15-index) [Looman 2015],] Positive: Vegetables; Legumes; Fruit; Nuts; Fish (fatty); Tea; Whole Grains; Filtered Coffee; Replace butter/hard fats with oils; Replace Refined with WholeGrains; Negative: Red Meat; Processed Meat; Sweetened beverages and fruit juices, Alcohol; Sodium. Neutral: Dairy Products [Excluded filtered coffee and sodium]; Methods: Index/Score | Follow-up: 6.3 [0.7] y mean, T2D; [underlined: Risk of T2D]: T1: PR 1, ref; T2: PR 0.86, 95% CI: 0.65, 1.13; T3: PR 0.76, 95% CI: 0.56, 1.02; P for trend=0.04; per 10 point increase: PR 0.96, 95%; CI: 0.88, 1.05; [underlined: Prediabetes]: T1: PR 1, ref; T2: PR 0.92, 95% CI: 0.78, 1.09; T3: PR 0.89, 95% CI: 0.75, 1.06; P for trend=0.18; per 10 point increase: PR 0.97, 95%; CI: 0.92, 1.01; [underlined: HbA1C:] x; [underlined: Glucose:] Change in FBG; T1, PR: 1, ref; T2, PR: −0.009, 95% CI: −0.073, 0.054; T3, PR: −0.016, 95% CI: −0.084, 0.052; Per 10 point higher: β= −0.012, 95%; CI: −0.034, 0.009; Summary: Inverse: DHD15-index & T2D; Inverse, NS: DHD15-index & preT2D Null: DHD15-index & change in FBG | - Did not account for: Race and/or ethnicity (predominantly white); Family History of diabetes; - Diet assessment: FFQ once; - Outcomes: Fasted/non-fasted OGTT collected and venous HbA1C determined; Different methods between cohorts and F/U were used (HPLC in HS but SRCEC in NHS at baseline then spot cards at F/U ); Pre-T2D and T2D defined by 2006 WHO, complementary to 2009 expert panel and 2011 WHO cut-offs; - Excluded coffee and sodium from DHD15; some missing OGTT and venous HbA1c in the NHS; Sensitivity analysis excluding HbA1c defined preT2D and T2D: for T2D, T3 vs. T1 PR: 0.63, 95% CI: 0.43, 0.90, P-trend=0.01; for preT2D: T3 vs. T1 PR: 0.75, 95% CI: 0.60, 0.93 (model remained sig after adjusting BMI); or excluding those w/ CVD, cancer, or both at baseline: for T2D, T3 vs. T1 PR: 0.53, 95% CI: 0.31, 0.87, P trend=0.007; for preT2D, T3 vs. T1 PR: 0.79, 95% CI: 0.59, 1.05 (similar results after adjusting BMI).; - Funding: NR
Dominguez, 2015^50^; Spain; Seguimiento Universidad de; Navarra (SUN) cohort; Analytic N=17292; Participant characteristics:; - Health:; - ○ BMI, kg/m2: 22.7 ± 3.3 to 23.9 ± 3.5; - ○ Family history of diabetes: 11-19%; - ○ HTN: 3-11%; HC: 8-24%; - ○ Smoking, current: 20-25%; former: 19-40%; - ○ Alcohol use: 5-9 g/d; - ○ PA: 19-26 MET-h/wk; - ○ Sitting: 5.5 to 5.9 h/d; - ○ TV: 4.5 to 4.7, h/d; - Race and/or Ethnicity: NR (Spanish); - SEP (Low, Intermediate, High DDS):; - Marital status, married: 38.7%; 51%; 59%; - Years of university education: 4.8±1.3; 5.1±1.5; 5.2±1.; Selection data: Included participants who had spent enough time in the study (>2.75 y) as to be able to complete and return F/U data; Excluded participants who did not meet the above criteria at F/U, reported extreme TEI, previous diabetes | Age at Dietary Pattern: 32.1 to 43.2y; [underlined: Dietary-Based Diabetes-Risk Score][underlined: (DDS) [Dominguez, 2015],] Positive: Vegetables; Fruit; Whole cereals; Nuts; Low-fat dairy; Fiber; PUFA; Coffee. Negative: Red meat; Processed meats; Sugar-sweetened beverages. Moderate: Alcohol; Methods: Index/Score | Follow-up: 9.2 y mean, T2D; [underlined: Risk of T2D]:; Low DDS, HR: 1, ref; Intermediate, HR: 0.43, 95% CI: 0.21, 0.89; High, HR: 0.32, 95% CI: 0.14, 0.69; P-trend= 0.019; DDS per 5-pt, HR: 0.85, 95% CI: 0.73, 0.98, P=0.026; DDS per 1-pt, HR: 0.96, 95% CI: 0.94, 0.99, P=0.029; Summary: Inverse: DDS & T2D | - Did not account for: Race and/or ethnicity; SEP (did marital status); - Diet assessment: FFQ once; - Outcomes: Self-reported T2D, confirmed with self-report of anti-diabetic meds (accuracy validated); - Sensitivity analyses High vs. low score, ♂: HR 0.31, 95% CI: 0.12, 0.76, P=0.011; in ♂: HR 0.39, 95% CI: 0.09, 1.70, P=0.21; in age > 50 y: HR 0.19, 95% CI: 0.07, 0.51, P=0.001; in age < 50 y: HR 0.68, 95% CI: 0.19, 2.40, P=0.56; in BMI ≥ 30: HR 0.18, 95% CI: 0.04, 0.75, P=0.018; in BMI< 30: HR 0.46, 95% CI: 0.18, 1.19, P=0.11; excluding cases diagnosed within first 2-y of F/U: HR 0.48, 95% CI: 0.19, 1.20, P=0.12.; - Funding: the Spanish Ministry of Health and European Regional Development Fund; the Navarra Regional Government; the Spanish Government
Dow, 2019^51^; Australia; AusDiab; Analytic N=6242; Participant characteristics:; - Health: 19.3% Ob (BMI≥ 30); 41.2% OW (BMI 25-30 kg/m2); 39.5% BMI <25 kg/m2; - Smoking, never: 59.8% ex-smoker: 28.7% current: 11.5%; - Family history of T2D: 18.1%; - WC health-risk: high 31.1%, increase 26.9, low: 42%; - PA: sedentary (<75 min): 15.1%, insufficient (75-149 min): 30.4%, sufficient (≥150 min): 54.6%; - HTN: 27.2%; - TG ≥ 2.0 mmol/L: 19.9%; - HDL cholesterol < 1.0 mmol/L: 9.3%; - Race and/or Ethnicity: NR (Australian); - SEP: Education: Secondary, trade, technician’s certificate or less: 66.1%; Bachelor’s degree, post-graduate, nursing or teaching qualification: 33.9%; Selection data: Eligible participants were≥25 years of age and residing at their address for ≥6 months; Excluded participants with diabetes at baseline, who did not participate in F/U, had incomplete dietary data, or extreme TEI values | Age at Dietary Pattern: 50.3 (12.5) y; [underlined: Australian Dietary Guidelines, 2013,] ([underlined: ADG-13]) [Dow, 2019], Positive: Vegetables and Legumes; Fruits; Grains, Dairy (milk, yogurt, cheese, alt.), Proteins (lean meats and poultry, fish, eggs, tofu, nuts/seeds, and legumes/bean); Neutral: Alcohol (2 or less drinks/day); Methods: Index/Score | Follow-up: 11.7 y median (2.0 to 13.1y), T2D; [underlined: Risk of T2D]:; ADG-13 1-3 pts: HR 0.93, 95% CI: 0.75, 1.16; ≥3 pts (strong adherence): HR 0.64, 95% CI: 0.39, 1.06; Summary: NS/Null: Adherence to Australian Dietary Guidelines, 2013 & T2D | - Did not account for: Race and/or ethnicity; Physical activity (analyzed as exposure), Smoking (analyzed as exposure), Anthropometry (WC-group analyzed as exposure),; - Diet assessment: FFQ once; - Outcomes: Fasted blood samples collected; T2D based on OGTT, FPG ≥ 7.0 mmol/l, 2h PG≥ 11.0 mmol/L or current Tx with anti-diabetes agends (insulin/oral hypoglycemic agent).; - Sensitivity analysing treating moderate alcohol as strong adherence instead of no alcohol: 1-3 pts, HR 0.80, 95% CI: 0.65, 0.99, ≥3 pts: HR 0.59, 95% CI: 0.36, 0.96;; - BMI or WC and physical activity were comined with diet to examine a “healthy behavior index” in this study.; - Funding: Cardiovasulaire, Obésité, Rein, Diabète Program; National Health and Medical Research Senior Fellowship; National Research Agency’s program “Investing in the Future”; IDEX Paris Saclay Nutriperso project;
Duan, 2022_L^52^; Netherlands; Lifelines cohort; Analytic N=61,869; Participant characteristics:; - Health: mean BMI: 26.1; FPG 4.95 mmol/L; HbA1C 5.54%; Family history of diabetes: 8.8% ; Risk drinking: 16.5%; PA recs, 150 min/wk: 59.2%; - Smoker: Never 45%; former 37%; current 17%; - Race and/or Ethnicity: NR (Dutch); - SEP: Education: low, 29%; middle, 40%; high, 31%; Selection data: Excluded those with diabetes at baseline; missing lifestyle data; missing f/u data; who reported development of T1D or GDM during f/u | Age at Dietary Pattern: 48y, mean (35 to 65y); [underlined: Lifelines Diet score (LLDS]) [Vinke, 2018], Positive: Vegetables; Fruit; Legumes and Nuts; Whole Grains; Fish; Oils and Soft Margarines; Unsweetened Dairy; Tea; Coffee; Negative: Red and processed meats; Sugar-sweetened beverages; Butter and Hard Margarines; Methods: Index/Score | Follow-up: ~3.4y, median; 41 months; [underlined: Risk of T2D]:; LLDS T1 v. T3 (ref), HR: 1.20, 95% CI: 0.99, 1.45; LLDS T2 v. T3 (ref), HR: 0.99, 95% CI: 0.83, 1.19; Summary: NS/Null: LLDS & T2D | - Did not account for: Race and/or ethnicity (all Dutch/Caucasian), or Physical Activity, Alcohol, Smoking as co-exposures; - Diet assessment: FFQ once; - Outcomes: Fasted blood samples HbA1C collected at 4th visit; Combination of self-report at 2nd & 3rd visits; measured FBG & HbA1C at 4th visit; T2D based on self-report of diagnosis since last survey or FBG ≥ 7 mmol/L; HbA1C ≥ 6.5% (48 mmol/L), 900 cases T2D; - Insufficient physical activity; smoking; and risk-drinking (>15g alcohol/d) were not associated w T2D in fully adjusted model when analyzed separated or as components of overall HLS; - Funding: European Union; Dutch Ministry of Health, Welfare, and Sport; Dutch Ministry of Economic Affairs; University Medical Center Groningen; University of Groningen; Provinces in the north of The Netherlands (Drenthe, Friesland, and Groningen)
Duan, 2021^53^; Netherlands; Lifelines cohort; Analytic N=64,777 ( ♀ 39000; ♂ 2577); Participant characteristics:; - Health: Baseline characteristics ♀ ; ♂:; - BMI, kg/m2: 25.4 ± 4.4; 26.0 ± 3.4; - WHR: 0.862 ± 0.070; 0.955 ± 0.066; - FBG, mmol/L: 4.77 ± 0.42; 5.00 ± 0.41; - HTN: 32.9%; 55.6%; - TG ≥ 1.70 mmol/L: 7.3%; 21.5%; - PA (moderate/vigorous), min./wk: 300 (120, 760); 385 (150, 1195); - Current smoker: 17.4%; 20.6%; - Alcohol use, g/d: 27 (2, 76); 106 (36, 215); - Race and/or Ethnicity: NR (northern Dutch); - SEP: University degree ♀ ; ♂: 31.1%; 34.9%; - High income (>€3000/mo)♀ ; ♂ : 28.6%; 34.8%; - Selection data: Included participants 18 to 65 y at baseline with valid dietary intake and blood data; Excluded participants with cancer and liver cirrhosis, as well as participants who took lipid modifying agents, corticosteroids for systemic use and anabolic steroids; nonfasting participants and participants with unreliable energy intake level; participants with any kinds of diabetes, including T1D or GDM or prediabetes at baselne; participants who lost to follow-up or without any valid follow-up data on diabetes, or who did not have anthropometric data | Age at Dietary Pattern: 43.2 ♀, 43.5 ♂ (18 to 65) y at baseline; ♀ Positive: Sugary beverages, Added sugar, Juice. Negative: Tea, Fruits, Vegetables, Nuts/seeds, Cereals, Dairy products (low fat, fermented, unsweetened), Fatty fish, Other Fish, high fat Cheese, Eggs ♂ Positive: Sugary beverages, Added sugar, Juice, Cofffee, Savory snacks. Negative: Tea, Fruits, Vegetables, Nuts/seeds, Cereals, Dairy products (low fat, fermented, unsweetened), Chocolate spreads and Bread products; Methods: RRR | Follow-up: ~3.5y (43 month mean), T2D; [underlined: Risk of T2D]: ♀ Q1, OR: 1, ref; ♀ Q2, OR: 0.97, 95% CI: 0.62, 1.51; ♀ Q3, OR: 1.16, 95% CI: 0.76, 1.79; ♀ Q4, OR: 1.46, 95% CI: 0.95, 2.25; ♀ Q5, OR: 1.57, 95% CI: 1.01, 2.44; ♀ P-trend=0.012; ♂ Q1, OR: 1, ref; ♂ Q2, OR: 1.11, 95% CI: 0.69, 1.77; ♂ Q3, OR: 1.19, 95% CI: 0.74, 1.89; ♂ Q4, OR: 1.21, 95% CI: 0.75, 1.93; ♂ Q5, OR: 1.65, 95% CI: 1.04, 2.62; ♂ P-trend=0.034; Summary: Positive: Dietary pattern in ♂ or ♀ & T2D | - Did not account for: Race and/or ethnicity (Northern Netherland); Family history of diabetes; - Diet assessment: FFQ once; - Outcomes: Fasted/non-fasted blood test at 2nd F/U; Self-report used at 1st and 2nd F/U, confirmed with blood test at 2nd F/U; T2D defined as FBG ≥ 7 mmol/L and/or HbA1C ≥ 6.5% (48 mmol/L); - Complete case analyses including missing class for missing data yielded stronger associations and larger confidence intervals than results from multiple imputation; - Funding: European Union’s Horizon 2020 research and innovation programme, Marie Sklodowska-Curie grant; Fonds Economische Structuurversterking, Samenwerkingsverband Noord Nederland, Ruimtelijk Economisch Programma
Duan, 2022 ^(Ultra)54^; Netherlands; Lifelines cohort; Analytic N=70421; Participant characteristics:; - Health: mean BMI, 26.2; HbA1C 5.55%; median UPF intake ~24.9% weight; - Race and/or Ethnicity: NR (Dutch); - SEP: Education: Low 30.4%, Middle 38.9%, High 30.3%; Selection data: Excluded participants with only baseline data; reported GDM or T1D during F/U, nonvalid/extreme dietary intake, who have prevalent T2D | Age at Dietary Pattern: 49.1y, mean; (35 to 70y); [underlined: ‘UPF’] Nova classification, group 4 [Monteiro, 2016]: starchy food and cereals like sliced bread and granola (22.1%); non-cheese dairy like chocolate milk and ice cream (13.7%); sugary beverages like lemonade or ice tea (9.7%); [underlined: ‘warm savory snack’]: high intake of fried snacks, fries, and snack sauce;; [underlined: ‘cold savory snack’]: high intake of cheese, deli meat, and savory spreads for crackers or French bread;; [underlined: ‘traditional Dutch cuisine’]: high intake of main meal items typical for the Dutch culture, such as sliced bread, lunch meat, and gravy; ‘[underlined: sweet snack]’: high intake of sweet biscuits/cookies, pastries, and chocolate; Methods: Index/Score (UPF) and Factor or cluster analysis (UPF) | Follow-up: 41mo; [underlined: Risk of T2D]:; UPF, Nova 4; Q1, OR: 1, ref; Q2, OR: 1.04, 95% CI: 0.87, 1.26; Q3, OR: 1.20, 95% CI: 0.99, 1.45; Q4, OR: 1.56, 95% CI: 1.27, 1.92; p-trend< 0.001; per 10%, OR: 1.17, 95% CI 1.09, 1.26,; p-trend<0.001; ‘warm savory snack’; Q1, OR: 1, ref; Q2, OR: 1.02, 95% CI: 0.86, 1.22; Q3, OR: 1.11, 95% CI: 0.92, 1.34; Q4, OR: 1.17, 95% CI: 0.96, 1.44; p-trend=0.097; cont. OR: 1.07, 95% CI: 1.00, 1.14;; p=0.057; ‘cold savory snack’; Q1, OR: 1, ref; Q2, OR: 1.04, 95% CI: 0.87, 1.23; Q3, OR: 1.20, 95% CI: 1.00, 1.42; Q4, OR: 1.20, 95% CI: 1.00, 1.44; p-trend=0.020; Cont. OR: 1.11, 95% CI: 1.04, 1.18; p=0.001; ‘traditional Dutch cuisine’; Q1, OR: 1, ref; Q2, OR: 1.03, 95% CI: 0.87, 1.23; Q3, OR: 1.11, 95% CI: 0.92, 1.33; Q4, OR: 1.07, 95% CI: 0.87, 1.31; p-trend=0.411; Cont. OR: 1.03, 95% CI: 0.95, 1.11 ; p=0.476; ‘sweet snack’; Q1, OR: 1, ref; Q2, OR: 0.75, 95% CI: 0.64, 0.88; Q3, OR: 0.68, 95% CI: 0.57, 0.81; Q4, OR: 0.69, 95% CI: 0.57, 0.84; p-trend< 0.001; Cont. OR: 0.87, 95% CI: 0.80, 0.94; p=0.001; Summary: Positive: Nova 4 (per 10%, Q4 v. Q1) & T2D; ‘warm savory snack’ (cont.; Q4 v. Q1) & T2D; ‘cold savory snack’(cont.; Q4 v. Q1) & T2D; Inverse: ‘sweet snack (cont., Q2, 3, 4) & T2D; NS/Null: ‘traditional Dutch cuisine’ & T2D | - Did not account for: Race/Ethnicity (Duthc); Family history of diabetes; - Diet assessment: FFQ once (baseline); - Outcomes: Fasted blood samples/HbA1C collected at T4; T2D from comination of selfreport at T2, T3, T4 and/or measured FBG ≥ 7 mmol/L or HbA1C ≥ 48 mmol/L (6.5%).; - Identified 1128 cases; Analyzed missing data via complete case and those LFU < 24mo; - Funding: European Union’s Horizon 2020 research and innovation programme, Marie Sklodowska-Curie grant; Fonds Economische Structuurversterking, Samenwerkingsverband Noord Nederland, Ruimtelijk Economisch Programma
Eguaras, 2017 ^55^; Spain; Seguimiento Universidad de; Navarra (SUN) cohort; Analytic N=18225; Participant characteristics:; - Health: Low adherence to MedDiet (≤4/9) and BMI<25; 25-40; or >30 kg/m2; - BMI, kg/m2: 21.6 ± 2.0; 26.9 ± 1.3; 32.4 ± 2.3; - PA, METs: 20.2 ± 21.7; 20.3 ± 21.9; 15.7 ± 18.2; - Smoking, current: 23.4%; 21.1%; 20.0% vs. former: 21.1%; 32.8%; 37.9%; - HC: 10.7%; 20.1%; 30.9%; - HTN: 2.5%; 10.3%; 21.5%; - CVD: 0.4%; 1.3%; 1.3%; - Cancer: 2.4%; 2.6%; 4.2%; - Depression: 4.8%; 3.4%; 2.2%; - TV, h/wk: 1.6 ± 1.2; 1.7 ± 1.2; 1.8 ± 1.2; - Alcohol use, g/d: 3.5-5.5; - High adherence to MedDiet (>4/9) and BMI<25; 25-40; or >30 kg/m2; - BMI, kg/m2: 21.8 ± 1.9; 26.9 ± 1.3; 32.7 ± 3.1; - PA, METs: 25.3 ± 25.6; 23.4 ± 22.8; 17.5 ± 17.1; - Smoking, current: 21.6%; 19.2%; 18.4% vs, former: 27.8%; 41.9%; 46%; - Hypercholesterolaemia: 14.7%; 30%; 35%; - HTN: 3.9%; 15%; 27.4%; - CVD: 0.7%; 2.4%;; - Cancer: ~3%; - Depression: ~4%; - TV, h/wk: 1.6 ± 1.2; 1.7 ± 1.1; 1.8 ± 1.2; - Race and/or Ethnicity: NR (Spanish); - SEP: By BMI (<25; 25-39; >30); - Marital Status, Single: 26-58%; Married: 39-69%; - University edu.: Graduate: 17%-27%; Postgrad. 49-53%; M.S. Degree: 8-9%; PhD: 9-13%; Selection data: Excluded participants who had diabetes at baseline, not remained in the cohort enough time for 2y F/U; extreme TEI | Age at Dietary Pattern: 38 y (mean) at baseline; [underlined: Mediterranean Diet Score (MDS)]; [underlined: [Trichopolou 2003]:]; [underlined: MDS], Positive: Vegetables; Legumes; Fruit, Nuts; Cereals; Fish; MUFA/SFA. Negative: Red and Processed Meat; Dairy Products. Neutral: Alcohol; Methods: Index/Score | Follow-up: 9.5 y median, T2D; [underlined: Risk of T2D:]; Low MDS, BMI <25, HR: 1, ref; BMI 25-30, HR: 4.07, 95% CI: 1.58, 10.50; BMI >30, HR: 17.70, 95% CI: 6.29, 49.78; High MDS, BMI <25, HR: 1, ref; BMI 25-30, HR: 3.13, 95% CI: 1.63, 6.01; BMI > 30, HR: 10.70, 95 % CI: 4.98, 22.99; p-int=0.002; Summary: Inverse: MDS & T2D | - Did not account for: Race/Ethnicity; Family history of diabetes; - Diet assessment: FFQ once (baseline); - Outcomes: Self-reported physician diagnosis, confirmed with self-report of details e.g., anti-diabetes meds, medical records; - Indirect analyses of MDS attenuating the association between high BMI & T2D; - Funding: European Research Council; the Spanish Government-Instituto de Salud Carlos III, the European Regional Development Fund, the Navarra Regional Government and the University of Navarra
Ericson, 2018^56^; Sweden; Malmo Diet and Cancer (MDC) cohort; Analytic N=25069; Participant characteristics:; - Health: Excluded participants with self-reported diabetes; - Characteristics by diet risk score: low; mid; high; - BMI, kg/m2: 25.4 ± 3.8; 25.6 ± 3.9; 26.0 ± 4.0; - Fasting blood glucose, mmol/L: 4.94 ± 0.7; 4.98 ± 0.7; 5.07 ± 0.9; - Fasting plasma insulin, mIU/L: 7.4 ± 7.3; 7.7 ± 8.0; 8.7 ± 7.6; - HOMA-IR: 1.52 ± 1.49; 1.58 ± 1.07; 1.81 ± 1.35; - Alcohol intake, g/day: 11.5 ± 12.0; 11.4 ± 12.6; 11.7 ± 13.8; - Smoking (ever): 65.2%; 61.3%; 58.5%; - Leisure time physical activity, high: 22.3%; 19.3%; 18.9%; - Race and/or Ethnicity: NR (Swedish); - SEP, % education 10y+: diet risk score low: 37.7%; mid: 31.6%; high: 26.3%; Selection data: Excluded participants based on self-reported diabetes, diabetes meds, or medical registries, who did not complete questionnaires or have available DNA and genotyped SNPs | Age at Dietary Pattern: 58.2 y mean, 45 to 74 y at baseline; [underlined: Diet Risk Score (DRS) [Ericson, 2018]]: Positive: Negative: Whole grains; Coffee. Positive: Processed meat (sausage and cured meat), SSB (energy containing sweeteners);; [underlined: Extended DRS] (eDRS): Negative: Vegetables and Fruit; Whole grains; Vegetables and Fruit; Dairy fermented; Fish, high-fat; Coffee. Positive: Processed meat (sausage and cured meat), SSB (energy containing sweeteners); Methods: Index/Score | Follow-up: 17 [5.6] y mean (range 0-24), T2D; [underlined: Risk of T2D]: DRS, Low, HR: 1, ref; ♀+♂; Medium, HR: 1.19, 95% CI: 1.09, 1.30; High, HR: 1.40, 95% CI: 1.26, 1.56; P-trend<0.0001; ♀; Medium, HR: 1.33, 95% CI: 1.18, 1.50; High, HR: 1.45, 95% CI: 1.26, 1.71; P for trend<0.0001; ♂; Medium, HR: 1.07, 95% CI: 0.95, 1.22; High, HR: 1.33, 95% CI: 1.14, 1.55; P for trend=0.0002; DRS+fruit&vegetable; Medium, HR: 1.23, 95% CI: 1.13, 1.33; High, HR: 1.37, 95% CI: 1.24, 1.51; ptrend<0.0001; ♀; Medium , HR: 1.33, 95% CI: 1.18, 1.48; High, HR: 1.45, 95% CI: 1.26, 1.67; ptrend<0.0001; ♂; Medium, HR: 1.15, 95% CI: 1.01, 1.30; High, HR: 1.29, 95% CI: 1.11, 1.49; ptrend=0.001; DRS+fermented dairy; Medium, HR: 1.21, 95% CI: 1.11, 1.32; High, HR: 1.36, 95% CI: 1.23, 1.50; p- trend<0.0001; ♀; Medium , HR: 1.32, 95% CI: 1.18, 1.48; High, HR: 1.51, 95% CI: 1.31, 1.73; p-trend<0.0001; ♂ Medium, HR: 1.10, 95% CI: 0.98, 1.26; ♂ High, HR: 1.22, 95% CI: 1.06, 1.41; ♂ P for trend=0.005; DRS + high-fat fish; ♀+♂ Medium, HR: 1.18, 95% CI: 1.09, 1.29; ♀+♂ High, HR: 1.36, 95% CI: 1.24, 1.51; ♀+♂ P- trend<0.0001; ♀Medium, HR: 1.30, 95% CI: 1.15, 1.46; ♀High, HR: 1.54, 95% CI: 1.34, 1.77; ♀P for trend<0.0001; ♂ Medium, HR: 1.07, 95% CI: 0.94, 1.20; ♂ High, HR: 1.21, 95% CI: 1.04, 1.40; ♂ P for trend=0.01; eDRS; Medium, HR: 1.18, 95% CI: 1.08, 1.30; High, HR: 1.39, 95% CI: 1.23, 1.56; P for trend<0.0001; ♀Medium, HR: 1.21, 95% CI: 1.07, 1.37; High, HR: 1.45, 95% CI: 1.23, 1.71; P for trend<0.0001; ♂ Medium, HR: 1.17, 95% CI: 1.00, 1.36; High, HR: 1.30, 95% CI: 1.14, 1.63; p- trend=0.001; Summary: Positive: DRS, eDRS & T2D | - Did not account for: Race and/or ethnicity (Swedish); Family history of diabetes; - Diet assessment: Diet history once (validated; interview + 7d menu + Q); - Outcomes: Combination of seven registries (90%) or exams (10%); diagnosis from FBG ≥ 7 mmol/L and/or 2+ HbA1C ≥ 6%; - Sensitivity analyses: model excluding BMI, replacing BMI with waist or body fat percent did not substantially change results; excluding individuals with dietary change in the past, and excluding individuals with prevalent cardiovascular disease at baseline did not change results either.; - Funding: the European Research Council; the Swedish Research Council; the Swedish Heart and Lung Foundation; the Region Skane, the Novo Nordic Foundation and the Albert Pahlsson Research Foundation
Ericson, 2019^57^; Sweden; Malmo Diet and Cancer; (MDC) cohort; Analytic N=2627; Participant characteristics:; - Health: 100% BMI < 25 without diabetes, CVD, or cancer; - Race and/or Ethnicity: NR (Iranian); - SEP: Academic education (%) across EDIH quantiles: 23 to 32% (p<0.001); across EDIP quantiles: 27 to 33% (p-trend=0.036); Selection data: Excluded those with diabetes/diabetes meds at baseline; history of Coronary events or stroke; substantial changes in diet; no longer living in Sweden | Age at Dietary Pattern: 45 to 74 y at baseline; [underlined: ‘Health-Conscious’:] Higher loadings for cottage cheese (♀) or cream (men), fibre-rich bread, fruits, vegetables, breakfast cereals, fish and low-fat yoghurt; lower loadings for low-fibre bread, red and processed meat, sugarsweetened beverages; [underlined: ‘Low-Fat Products’]: Higher loadings for low-fat margarines, low-fat milk, low-fat yoghurt; lower loadings for butter; [underlined: ‘Dressing-Vegetables’]: Higher loadings for dressing/oils, vegetables, poultry, salty snacks, rice/pasta, fried potatoes, cheese; lower loadings for boiled potatoes, jam/sugar; Methods: Factor or cluster analysis | Follow-up: 6.2 y, mean; [underlined: Risk of T2D (Q1, HR 1 REF)]:; ‘Health conscious ♀; ♀Q2, HR: 1.09, 95% CI: 0.91,1.31; ♀Q3, HR: 0.92, 95% CI: 0.76,1.11; ♀Q4, HR: 0.96, 95% CI: 0.79,1.16; ♀Q5, HR: 0.75, 95% CI: 0.61, 0.92; ♀p-trend=0.003; p-trend, cont.=0.003; ♂ Q2, HR: 0.98, 95% CI: 0.81, 1.17; ♂ Q3, HR: 0.95, 95% CI: 0.79, 1.15; ♂ Q4, HR: 0.83, 95% CI: 0.68, 1.00; ♂ Q5, HR: 0.82, 95% CI: 0.68, 1.00; ♂ p-trend=0.01; p-trend, cont.=0.01; Low-fat products ♀; ♀Q2, HR: 1.03, 95% CI: 0.84,1.26; ♀Q3, HR: 0.75, 95% CI: 0.61,0.92; ♀Q4, HR: 1.02, 95% CI: 0.84,1.26; ♀Q5, HR: 1.19, 95% CI: 0.98,1.45; ♀p-trend= 0.1; p-trend, cont.=0.24; ♂ Q2, HR: 1.07, 95% CI: 0.88,1.30; ♂ Q3, HR: 0.98, 95% CI: 0.80,1.19; ♂ Q4, HR: 1.1, 95% CI: 0.90,1.33; ♂ Q5, HR: 1.15, 95% CI: 0.96,1.40; ♂ p-trend= 0.12; p-trend, cont.=0.1; Dressing and vegetables ♀; ♀Q2, HR: 1.02, 95% CI: 0.85,1.22; ♀Q3, HR: 0.92, 95% CI: 0.76,1.11; ♀Q4, HR: 0.96, 95% CI: 0.79,1.18; ♀Q5, HR: 1.12, 95% CI: 0.91,1.37; ♀p-trend= 0.54; p-trend, cont.=0.33; ♂ Q2, HR: 0.92, 95% CI: 0.76,1.12; ♂ Q3, HR: 1.06, 95% CI: 0.87,1.28; ♂ Q4, HR: 1, 95% CI: 0.82,1.21; ♂ Q5, HR: 1.09, 95% CI: 0.90,1.33; ♂ p-trend= 0.25; p-trend, cont.=0.24; Summary:; Inverse: ‘Health conscious’ ♀ or ♂ & Risk of T2D;; Inverse: ‘Low-fat products ♀ (Q3 v. Q1 only) & Risk of T2D; Null, NS: ‘Low-fat products ♀ or ♂ & Risk of T2D; Null, NS: ‘Dressing and vegetables ♀ or ♂ & Risk of T2D | - Did not account for: Race/Ethnicity, Family history of diabetes; - Diet assessment: Diet history once (validated; interview + 7d menu + Q); - Outcomes: Combination of seven registries (90%) or exams (10%); diagnosis from FBG ≥ 7 mmol/L and/or 2+ HbA1C ≥ 6%; - Funding: Swedish Research Council, the Region Skåne, the Skåne University Hospital, the Novo Nordic Foundation, the Albert Påhlsson Research Foundation
Esfandiar, 2022^58^; Iran; Tehran Lipid and Glucose; Study (TLGS); Analytic N=6112; Participant characteristics:; - Health: BMI mean, 27.1 [4.5]; WC: 89.8 cm; Current smokers 22.6%; - Race and/or Ethnicity: NR (Iranian); - SEP: NR; Selection data: Excluded those with pregnancy/lactating, extreme energy intake, baseline diabetes; incomplete/missing data or LFU | Age at Dietary Pattern: 41.2y; Healthy Eating Index (HEI-2015); [Krebs-Smith 2018]; Mediterranean Diet Score (MDS); [Trichopoulou 2003]; DASH Score [Fung, 2008]:; [underlined: HEI-2015]: Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; PUFA+MUFA/SFA. Negative: Refined Grains; Added Sugars; SFA; Sodium; [underlined: MDS]: Positive: Vegetables; Legumes; Fruit, Nuts; Cereals; Fish; MUFA/SFA. Negative: Red and Processed Meat; Dairy Products. (Excluded Alcohol); [underlined: DASH score]: Positive: Vegetables; Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Sodium; Methods: Index/Score | Follow-up: 6.6y, mean; [underlined: Risk of T2D]: HEI-2015 & T2D; Q2, HR: 1.26, 95% CI: 0.99, 1.62; Q3, HR: 1.07, 95% CI: 0.73, 1.38; Q4, HR: 1.20, 95% CI: 0.94, 1.53; p-trend=0.21; MDS & T2D; Q2, HR: 1.02, 95% CI: 0.82, 1.26; Q3, HR: 0.89, 95% CI: 0.63, 1.24; Q4, HR: 1.06, 95% CI: 0.87, 1.30; p-trend=0.52; DASH & T2D; Q2, HR: 0.93, 95% CI: 0.72, 1.20; Q3, HR: 0.89, 95% CI: 0.69, 1.15; Q4, HR: 1.13, 95% CI: 0.88, 1.46; p-trend=0.23; Summary: NS/Null: HEI-2015; MDS; DASH & T2D | - Did not account for: Race and/or ethnicity (Iranian); Anthropometry; Family history of diabetes; - Diet assessment: FFQ once (baseline); - Outcomes: Fasted (12-14h) blood samples; T2D cases FBG ≥ 126 mg/dL; 2-h OGTT 75g, ≥ 200 mg/dL or Tx with antidiabetes meds; - 549 T2D cases; Data for each dietary pattern & T2D in all participants NR (only sexstratified values reported in Supplemental Table 1, all NS); - Funding: Shahid Beheshti University of Medical Sciences
Farhadnejad, 2021^59^; Iran; Tehran Lipid and Glucose; Study (TLGS); Analytic N=3734; Participant characteristics:; - Health: 100% BMI < 25 without diabetes, CVD, or cancer; - Race and/or Ethnicity: NR (Iranian); - SEP: Education by EDIH; EDIR, N (%); - Q1, 215 (23.0); 249 (26.9); - Q2, 273 (29.3); 270 (29.2); - Q3, 301 (32.3); 304 (33.0); - Q4, 300 (32.2); 266(28.8); - p-trend<0.001; p-trend=0.036; Selection data: Excluded those with underreporting or over-reporting dietary intakes; on hyperglycemic diets; with history of MI, cerebral vascular accident, or cancer; with diabetes; with BMI <18.5 or >40; lactating and pregnant ♀; missing F/U data | Age at Dietary Pattern: ≥20 y at baseline; Empirical dietary index for hyperinsulinemia (EDIH) or insulin restistance (EDIR) [Tabung, 2016]; [underlined: EDIH:] Positive: Red meat; Processed meat; Poultry; Tomatoes; French fries, Fish (other than dark-meat fish); Lowfat dairy; Eggs; High-energy beverages (cola and other carbonated beverages with sugar, fruit drinks); Low-energy beverages; Margarine; Cream soups; Negative: Green leafy vegetables; Whole fruit; High-fat dairy products; Coffee; Wine; [underlined: EDIR] [13 instead of 18 foods]: Positive: Tomatoes; Other vegetables; Fruit juice; Refined grains; Red meat; Margarine; Processed meat; Fish. Negative: Vegetables (green leafy); Vegetables (dark yellow); Nuts; Dairy products (high-fat), Coffee; Methods: Index/Score | Follow-up: 6.2 y, mean; [underlined: Risk of T2D]: EDIH & Incident T2D; Q1, OR: 1.00, ref; Q2, OR: 1.39, 95% CI: 0.96, 2.01; Q3, OR: 0.86. 95% CI: 0.58, 1.29; Q4, OR: 0.95, 95% CI: 0.63, 1.44; p-trend=0.377; EDIR & Incident T2D; Q1, OR: 1.00, ref; Q2, OR: 1.14, 95% CI: 0.76, 1.72; Q3, OR: 1.45, 95% CI: 0.96, 2.19; Q4, OR: 1.58, 95% CI: 1.03, 2.44; p-trend=0.025; Summary: Positive: EDIP & T2D; NS/Null (Inverse): EDIH & T2D | - Did not account for: Race/Ethnicity; Family history of diabetes; - Diet assessment: FFQ once; - Outcomes: Fasted (12-14h) blood samples and 2-h OGTT collected; T2D defined by ADA criteria as FPG ≥ 126 mg/dl or 2-h post 75-g glucose load ≥ 200 mg/dl or use of anti-diabetes meds; - Notable magnitude: 58% higher T2D risk from EDIR but EDIH weak/ns inverse; - Funding: Shahid Beheshti University of Medical Sciences
Filippatos, 2016^60^; Greece; ATTICA; Analytic N=1875; Participant characteristics:; - Health: Those with IFG were more likely to be male, older, smoker, HTN, HC, and higher BMI, WC, Blood pressure and Cholesterol and TG, lower HDL-C; Those with higher MedDiet adherence were more likely to be female, younger, and lower BMI, WC, TG and less frequent HTN, HC, and higher HDL-C.; - Race and/or Ethnicity: NR (Greek); - SEP: Education, mean y ~ 12.3 (IFG) or 12.4 (normal glucose); Selection data: All with IFG=100-125 mg/dl; Excluded those with CVD, chronic viral infection, missing CVD data, and T2D at baseline | Age at Dietary Pattern: ≥18 y at baseline; [underlined: Mediterranean-based Diet Score (MedDietScore)] [Panagiotakos 2007]: Positive: Vegetables; Potatoes; Legumes; Fruit; Whole Grains; Fish; Olive Oil. Negative: Red and Processed Meat; Poultry; Full-Fat Dairy; Alcohol; Methods: Index/Score | Follow-up: 10y; [underlined: Risk of T2D]: MedDietScore <25, ref; MedDietScore 26-35, OR: 0.31, 95% CI: 0.13, 0.83;; MedDietScore >35,OR: 0.13, 95% CI: 0.03, 0.63; per unit, OR: 0.99, 95% CI: 0.93, 1.05; Summary: Inverse: MedDietScore & 10-y T2D incidence | - Did not account for: Race and/or ethnicity; TEI; - Diet assessment: FFQ once; - Outcomes: Fasted (12h+) blood samples collected; T2D defined by ADA criteria as FPG >125 mg/dl or use of anti-T2D meds; IFG by FBG 100-125 mg/dl;; - Funding: Coca-Cola SA
Freisling, 2020^61^; Denmark, Germany, Italy, the Netherlands, Spain, Sweden, UK;; EPIC; Analytic N=291,778; Participant characteristics:; - Health: Excluded those w/ cancer, MI and angina, stroke, and T2D at baseline; - Race and/or Ethnicity: NR; - SEP: NR; Selection data: Excluded those with prevalent cancer, MI and angina, stroke, and T2D at baseline; with missing data on T2D status at baseline; missing education, smoking, or physical activity data | Age at Dietary Pattern: 35 to 70 y at baseline; [underlined: relative Mediterranean Diet Score][underlined: (rMED) [Buckland 2009],] Positive: Vegetables (not potatoes); Legumes; Fruit, Nuts, and Seeds (not juice); Whole Grains, Refined Flour, Pasta, Rice, Bread, Grains; Fish; Olive Oil. Negative: Total and Processed Meat. Neutral: Alcohol; Methods: Index/Score | Follow-up: 10.7 y, median (mean ♂: 9.2-13.4 y and in ♀: 9.0-13.3 y (varied by country)); [underlined: Risk of T2D]: T2D (fatal + non-fatal); Per 3-pt, HR: 0.91, 95% CI: 0.89, 0.94; Summary: Inverse: rMED & T2D | - Did not account for: Race and/or ethnicity, Physical activity (analyzed as Co-E), Anthropometry (analyzed as CoE), Smoking (analyzed as Co-E); - Diet assessment: Questionnaires once (validated; country/centre-specific) at baseline; - Outcomes: Combination of selfreport, linkage to registries, hospital/mortality data; - Funding: French Ministry of Health, French National Cancer Institute, Cancéropôle Ile-deFrance
Fung, 2021^62^; USA; NHS II; Analytic N=88,520; Participant characteristics:; - Health: GDQS quantiles ranged in mean BMI ~24.2-24.6 and current smokers ~ 9-18%; - Race and/or Ethnicity: NR; - SEP: NR, all health professionals; Selection data: Included only ♀. Excluded those with diabetes, GDM, cancer, or CVD at baseline; who died before the first dietary assessment; who did not complete additional questionnaires beyond baseline; who reported implausible energy intakes at baseline; pregnant during a questionnaire period (excluded from that questionnaire period only) | Age at Dietary Pattern: 25 to 42 y at baseline; modified Global Diet Quality Score (GDQS) [Bromage, 2021]; Alternative HEI (AHEI)-2010 [Chiuve 2012]; Minimum Dietary Diversity for Women [MDD-W; Gicevic, 2018]; [underlined: GDQS:] Positive: Vegetables (dark green leafy); Vegetables (Cruciferous); Vegetables (Deep Orange); Vegetables (Other); Tubers (Deep Orange); Fruit (Citrus); Fruit (Deep Orange); Fruit (Other); Legumes; Nuts and Seeds; Whole Grains; Fish and Shellfish; Poultry and Game; Low-fat Dairy; Eggs; Oils (Liquid). Negative: High-fat Dairy; Red meat; Processed meat; Refined grains and baked goods; Sweets and ice cream; SSBs; Juice; White roots and tubers; Purchased deep fried foods; [underlined: AHEI-2010]: Positive: Vegetables (not potatoes, French fries); Fruit; Legumes; Whole Grains; Oily fish; PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol; [underlined: MDD-W]: Positive: Vegetables (starchy) and Grains; Vegetables (green leafy); Vegetables & Fruit ("Vit. A-rich"); Vegetables (Other); Fruit (Other); Nuts and Seeds; Dairy; Animal flesh; Eggs; Methods: Index/Score | Follow-up: ≤26 y f/u; [underlined: Risk of T2D]: GDQS (all) & T2D; (incidence); Q1, HR: 1, ref; Q2, HR: 0.91, 95% CI: 0.84, 0.97; Q3, HR: 0.94, 95% CI: 0.87, 1.01; Q4, HR: 0.87, 95% CI: 0.80, 0.94; Q5, HR: 0.83, 95% CI: 0.76, 0.91; p-trend<0.001; GDQS (< 50 y)& T2D (incidence); Q1, HR: 1, ref; Q2, HR: 0.86, 95% CI: 0.76, 0.98; Q3, HR: 1.00, 95% CI: 0.88, 1.13; Q4, HR: 0.90, 95% CI: 0.79, 1.02; Q5, HR: 0.85, 95% CI: 0.73, 0.98; p-trend=0.02; GDQS (≥ 50 y)& T2D (incidence); Q2, HR: 0.93, 95% CI: 0.85, 1.02; Q3, HR: 0.91, 95% CI: 0.82, 1.00; Q4, HR: 0.85, 95% CI: 0.77, 0.94; Q5, HR: 0.82, 95% CI: 0.74, 0.91; p-trend<0.001; AHEI-2010 (all)& T2D (incidence); Q2, HR: 0.95, 95% CI: 0.89, 1.02; Q3, HR: 0.88, 95% CI: 0.82, 0.95; Q4, HR: 0.80, 95% CI: 0.74, 0.87; Q5, HR: 0.62, 95% CI: 0.56, 0.68; p-trend<0.001; AHEI-2010 (<50 y)& T2D (incidence); Q2, HR: 0.91, 95% CI: 0.81, 1.02; Q3, HR: 0.89, 95% CI: 0.78, 1.00; Q4, HR: 0.76, 95% CI: 0.66, 0.88; Q5, HR: 0.64, 95% CI: 0.55, 0.75; p-trend<0.001; AHEI-2010 (≥ 50 y)& T2D (incidence); Q2, HR: 0.97, 95% CI: 0.89, 1.06; Q3, HR: 0.88, 95% CI: 0.80, 0.96; Q4, HR: 0.83, 95% CI: 0.75, 0.91; Q5, HR: 0.61, 95% CI: 0.54, 0.69; p-trend<0.001; MDD-W (all) & T2D (incidence); Q2, HR: 1.08, 95% CI: 0.99, 1.17; Q3, HR: 1.04, 95% CI: 0.95, 1.13; Q4, HR: 1.11, 95% CI: 1.01, 1.21; Q5, HR: 1.09, 95% CI: 0.99, 1.21; p=0.88; MDD-W (>50y) & T2D (incidence); Q2, HR: 1.10, 95% CI: 0.96, 1.26; Q3, HR: 0.98, 95% CI: 0.84, 1.13; Q4, HR: 1.09, 95% CI: 0.93, 1.27; Q5, HR: 1.10, 95% CI: 0.93, 1.29; p-trend=0.64; MDD-W (≥ 50 y) & T2D (incidence); Q2, HR: 1.07, 95% CI: 0.97, 1.19; Q3, HR: 1.08, 95% CI: 0.97, 1.21; Q4, HR: 1.12, 95% CI: 1.00, 1.26; Q5, HR: 1.10, 95% CI: 0.97, 1.24; p-trend=0.82; Summary: Inverse: GDQS & T2D (all age groups); Inverse: AHEI-2010 & T2D (all age groups) NS/Null: MDD-W & T2D (all age groups) | - Did not account for: Race and/or ethnicity, Alcohol (in GDQS); SEP (all health professionals); - Diet assessment: FFQ every 4y; - Outcomes: Self-report confirmed with reported f/u based on NDDG Group criteria: classic symptoms and FPG ≥ 7.8 mmol/L (or 7 for cases post1998 via ADA criteria) or NF ≥ 11.1 mmol/L; or 2+ elevated BG (F, or NF) on different occasions; or Tx with antidiabetes agents; - Adjustment for multiple testing NR; - Funding: FHI Solutions, NIH
Galbete, 2018^63^; Germany; EPIC-Potsdam; Analytic N=23411; Participant characteristics:; - Health: 56% OW/Ob (BMI 25+); 46% HTN; 51% current or former smokers; - Race and/or Ethnicity: NR (German); - SEP: Education: 38% University degree; Selection data: All free of T2D, MI, stroke, or cancer at baseline; Excluded if missing/implausible data | Age at Dietary Pattern: 49.8 y, mean (35 to 65y, at entry; Nordic diet score [Galbete, 2018]; literature Mediterranean Diet Score (LitMDS) [Sofi 2014]; Pyramid Mediterranean Diet Score (PyrMDS) [Tong 2016]; [underlined: Nordic diet score]: Positive: Cabbage and cruciferous vegetables; Root Vegetables; Berries; Apples and Pears; Whole grain and Rye Bread; Fish; Low-fat Dairy products; Potatoes; Vegetable fats (not olive oil); [underlined: "tMDS"= LitMDS]: Positive: Vegetables; Legumes; Fruit and Nuts; Cereals; Fish; Olive Oil. Negative: Meat; Dairy Products. Neutral: Alcohol; [underlined: PyrMDS]: Positive: Vegetables; Legumes; Fruit; Nuts; Cereals; Fish; White Meat; Eggs; Dairy; Olive Oil. Negative: Potato; Red Meat; Processed Meat; Sweets; Alcohol; Methods: Index/Score | Follow-up: 10.6y; [underlined: Risk of T2D]:; Nordic, Moderate v. low, HR: 1.02, 95% CI: 0.89, 1.17; High v. low, HR: 1.01, 95% CI: 0.87, 1.18, ptrend=0.827;; per-SD, HR: 1.0, 95% CI: 0.94, 1.07;; per-unit, HR: 1.0, 95% CI: 0.98, 1.02; tMDS, Moderate v. low, HR: 0.92, 95% CI: 0.81, 1.04; High v. low, HR: 0.84, 95% CI: 0.73, 0.97, p-trend=0.019; per-SD, HR: 0.93, 95% CI: 0.88, 0.98; per-unit, HR: 0.97, 95% CI: 0.95, 0.99; PyrMDS, Moderate v. low, HR: 0.9, 95% CI: 0.79, 1.02; High v. low, HR: 0.8, 95% CI: 0.70, 0.92, p-trend=0.001; per-SD, HR: 0.92, 95% CI: 0.87, 0.97; per-unit, HR: 0.93, 95% CI: 0.89, 0.97; Summary: Inverse: PyrMDS or tMDS (LitMDS) & T2D; NS/Null: Nordic & T2D | - Did not account for: Race and/or ethnicity; Family history of diabetes; - Diet assessment: FFQ once (baseline); referenced with subset of 24-h recalls; - Outcomes: Self-report (of condition/meds) and linkage to registries then all cases verified by physicians/registries; - Funding: German Federal Ministry of Education and Research (NutriAct – Competence Cluster Nutrition Research Berlin-Potsdam)
Gao, 2022^64^; United Kingdom; BIOBANK; Analytic N=120343; Participant characteristics:; - Health: 18% Ob, 41% OW; 40% BMI 18.5 to 25 (mean BMI 26.5);; - Other: 16% family history of diabetes; 23% HTN; 5% CVD; 13.5% High cholesterol;; - Race and/or Ethnicity: 96.8% White; - SEP: Townsend Deprivation Index, Quntiles: 20% Q1, 20% Q3, 20% Q5, 0.1% missing; Education 52% ≥ college degree; Selection data: Excluded those with <2 diet assessments, diabetes before baseline or previous diet assessment, pregnancy, implausible energy intake, missing BMI data. | Age at Dietary Pattern: 37 to 73y; ‘DP1’: high intakes of chocolate and confectionery, butter, low-fiber bread, and sugars and preserves; low intakes of fruit and vegetables ‘DP2’: high intakes of sugar-sweetened beverages, fruit juice, table sugars and preserves; low intakes of high-fat cheese and butter; Methods: RRR: response vars energy density, SFA, free sugars, fiber density | Follow-up: 8.4y (after last assessment; 11.2y median); [underlined: Risk of T2D]:; DP1 & T2D; total, HR: 1.09, 95% CI: 1.06, 1.12; Q1, HR: 1.00, ref; Q2, HR: 1.13, 95% CI: 1.04, 1.23; Q3, HR: 1.19, 95% CI: 1.10, 1.30; Q4, HR: 1.25, 95% CI: 1.16, 1.35; Q5, HR: 1.38, 95% CI: 1.27, 1.49; p-trend<0.001; DP2 & T2D; total, HR: 1.03, 95% CI: 0.99, 1.06; Q1, HR: 1.00, ref; Q2, HR: 0.97, 95% CI: 0.89, 1.05; Q3, HR: 1.01, 95% CI: 0.93, 1.10; Q4, HR: 0.90, 95% CI: 0.82, 0.98; Q5, HR: 1.04, 95% CI: 0.96, 1.12; p-trend=0.818; Summary: Positive: DP 1 & T2D; NS/Mixed: DP2 & T2D | - Did not account for: N/A (all); - Diet assessment: 24h recalls over 4 cycles (DP from average of 2 surveys); - Outcomes: T2D based on registry (hospital/death); - Identified 2878 cases; - Funding: National Institute of Health Research (NIHR) Applied Research Centre
Glenn, 2023^65^; USA; Women Health Initiative (WHI); Analytic N=145299; Participant characteristics:; - Health: mean BMI ~26-28.6 across DP quantiles (OW/Ob); 100% postmenopause; - Race and/or Ethnicity: White: ~7492%; African-American: ~5-16%; Asian: ~2-4% ; Hispanic: 2-6%; - SEP: Education 55-81% college+; Married/partnered: ~60-65%; Selection data: Included ♀ who were postmenopause and free of diabetes at baseline ; excluded those with missing diet or lifestyle data, or with implausible energy intake | Age at Dietary Pattern: ~62 to 64y, mean across quantiles (50 to 79y); Alternate Med Diet Score (aMED) [Fung 2005]: Positive: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA/SFA. Negative: Red and Processed Meat.; DASH diet [Fung, 2008]: Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Sodium; Methods: Index/Score | Follow-up: 16y, median; [underlined: Risk of T2D]: DASH & T2D; Q1, HR: 1, ref; Q2, HR: 0.93, 95% CI: 0.88, 0.98; Q3, HR: 0.88, 95% CI: 0.84, 0.93; Q4, HR: 0.81, 95% CI: 0.77, 0.86; Q5, HR: 0.78, 95% CI: 0.72, 0.83; perSD, HR: 0.92, 95% CI: 0.90, 0.93; p-trend<0.001 aMED & T2D; Q1, HR: 1, ref; Q2, HR: 0.99, 95% CI: 0.94, 1.05; Q3, HR: 0.97, 95% CI: 0.92, 1.02; Q4, HR: 0.93, 95% CI: 0.88, 0.99; Q5, HR: 0.88, 95% CI: 0.83, 0.94; perSD, HR: 0.94, 95% CI: 0.93, 0.96; p-trend<0.001; Summary: Inverse: DASH & T2D; Inverse: aMED & T2D | - Did not account for: N/A (all); - Diet assessment: FFQ once; validated with 7-d diet records; - Outcomes: Self-report of physician Tx T2D with insulin/oral meds (validated); - Identified 13943 cases; Notably narrow CIs; Excluded data on Portfolio diet based on nutrients and not foods; - Funding: NHLBI, NIH
Glenn, 2021^66^; Spain; PREDIMED-Plus; Analytic N=6874; Participant characteristics:; - Health: 100% with OW or Ob and 3+ MetSyn criteria: 93-94% HTN; 75-77% HC; 29-32% diabetes; 5053% Statin-Tx; 76-79% Anti-HTN meds; 25-28% anti-diabetes meds; - Race and/or Ethnicity: ~97-98% European descent; - SEP: Education: 20-23% college; 26-32% HS/2nd; 46-51% primary or less; Selection data: Included those with OW/Ob and high-CMR (3+ MetSyn criteria); Excluded those with implausible/missing dietary intake | Age at Dietary Pattern: 65y, mean; [underlined: DASH diet [Fung, 2008],] Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Sodium; Methods: Index/Score | Follow-up: 1y; [underlined: HbA1C:] DASH & HbA1C %; Q1, β: 0, ref; Q2, β: −0.02, 95% CI: −0.04, 0.01; Q3, β: −0.03, 95% CI: −0.05, −0.01; Q4, β: −0.07, 95% CI: −0.09, −0.04; p-trend<0.001; perSD, β: −0.03, 95% CI: −0.04, −0.02;; p<0.001; [underlined: Glucose:] DASH & FPB, mg/DL; Q1, β: 0, ref; Q2, β: −0.86, 95% CI: −1.65, −0.05; Q3, β: −1.61, 95% CI: −2.46, −0.76; Q4, β: −2.14, 95% CI: −3.04, −1.24; p-trend<0.001; perSD, β: −0.84, 95% CI: −1.18, −0.51;; p<0.001; Summary: Inverse: DASH & HbA1C and FPG | - Did not account for: N/A (all); - Diet assessment: FFQ at baseline, 6mo, 1y; - Outcomes: Fasted (ON) blood samples for HbA1C & FPG; - Funding: Fondo de Investigacion para la Salud (FIS) and cofunded by European Union ERDF/ESF
Hirahatake, 2019^67^; USA; CARDIA; Analytic N=4719; Participant characteristics:; - Health: BMI, kg/m2: 23.5-25.1; - Family history of diabetes: 12-20%; - FBG, mmol/L: ~4.6; - Smoking status, current: 20-38%; - Smoking status, former: 6-21%; - Alcohol use: 10 to 14 mL/d; - PA: 376-475 units/wk; - Race and/or Ethnicity: White % across quantiles ranged from 25% to 80% (study recruited only Black and White participants); - e.g., DGA 2015 score Q1: 25.1%, Q2: 40.1%, Q3: 55.8%, Q4: 79.8%; - SEP: Education, y: across DPs ~13-15y mean; - DGA 2015 score Q1: 13.0 ± 4.7, Q2: 13.6 ± 4.1, Q3: 14.2 ± 3.2, Q4: 15.1 ± 3.3; Selection data: Recruited black and white men and ♀ aged 18-30 years from communities in four U.S. cities. Excluded participants with diagnosed diabetes at baseline, missing baseline or F/U diabetes status, missing baseline dietary data, without F/U data, or who reported extreme TEI | Age at Dietary Pattern: 18 to 30 y; Dietary pattern:; [underlined: 2015 Dietary Guidelines for][underlined: Americans, DGA-2015:] Positive: Vegetables; Legumes and Nuts; Fruits; Whole Grains; Seafood; Low-or NonFat Dairy products. Negative: Red and Processed Meat; Sugar-sweetened food and drinks; Refined grains. Moderate: Alcohol [excluded oil, poultry, coffee and tea]; [underlined: A Priori Diet Quality Score, APDQS] [underlined: [Sjitmsa, 2012]:] Positive: Vegetables; Legumes; Fruit; Nuts, Seeds; Whole Grains; Fish; Low-Fat Dairy; Vegetable Oil; Beer, Wine, Liquor; Tea, Coffee. Negative: Fried potatoes; High-fat meat; High-Fat Dairy; Desserts; Sugarsweetened soft drinks; Butter; Fried Foods; Salty Snacks; Neutral: Potatoes; Fruit Juices; Refined grains; Eggs; Shellfish; Lean meat; Margarine; Chocolate & Diet Soft Drinks; [underlined: Paleolithic Score] [Whalen 2014][underlined: ,] Positive: Vegetables; Fruit and Vegetable Diversity; Fruit; Nuts; Fish; Lean Meat; Calcium (from non-dairy foods). Negative: Grains and Starches; Baked Goods; Red and Processed Meat; Dairy Foods; Alcohol; Sodium; [underlined: Empty Calories [Hirahatake, 2019]] [underlined: (EC):] Positive: Alcohol; Butter; Margarine; Chocolate; Dairy dessert; Fried foods; Fried potatoes; Fruit juice; Grain dessert; Refined grains; Salty snacks; Sugar-sweetened beverages; “sweet extra”; Methods: Index/Score | Follow-up: 25.3 [8.3] y mean [SD], T2D; [underlined: Risk of T2D]:; DGA-2015; Q2: HR 0.96, 95% CI: 0.78, 1.17; Q3: HR 0.90, 95% CI: 0.71, 1.13; Q4: HR 0.88, 95% CI: 0.66, 1.17; per SD: HR 0.94, 95% CI: 0.84, 1.05; P trend=0.28; Paleolithic score; Q1: HR 1.0, ref; Q2: HR 0.92, 95% CI: 0.74, 1.15; Q3: HR 1.00, 95% CI: 0.80, 1.26; Q4: HR 1.07, 95% CI: 0.83, 1.37; per SD: HR 1.02, 95% CI: 0.93, 1.12; P trend=0.72; APDQS; Q1: HR 1.0, ref; Q2: HR 0.77, 95% CI: 0.63, 0.94; Q3: HR 0.74, 95% CI: 0.59, 0.92; Q4: HR 0.55, 95% CI: 0.41, 0.74; per SD: HR 0.78, 95% CI: 0.70, 0.86; P trend<0.0001; EC; Q1: HR 1.0, ref; Q2: HR 1.08, 95% CI: 0.87, 1.34; Q3: HR 0.93, 95% CI: 0.74, 1.17; Q4: HR 0.86, 95% CI: 0.68, 1.11; per SD: HR 0.95, 95% CI: 0.87, 1.04; P trend=0.28; Summary:; Inverse: APDQS & T2D; NS (Inverse) 2015 DGAI & T2D; NS/Null: Palaeo & T2D; EC scores & T2D | - Did not account for: N/A (all); - Diet assessment: Diet history at 0y, 7y, and 20y (validated; cumulative average (0 and 7y; 0, 7, and 20y)); - Outcomes: Clincally assessed at F/U years 0, 7, 10, 15, 20, 25, and 30; T2D defined as selfreported use of anti-diabetic agents, FBG ≥ 7 mmol/L (126 mg/dl), 2h-OGTT ≥ 11.1 mmol/L (200 mg/dL) and/or HbA1C ≥ 48 mmol/L and may have included T1D.; - N=680 (14.4%) cases identified; Stratified analysis: In Non-smokers, Inverse DGA-2015 per-SD & T2D: HR 0.86, 95% CI: 0.74, 0.99; In participants with a college degree+, Inverse DGA-2015 per-SD & T2D, HR 0.75, 95% CI: 0.61, 0.92; inverse association for EC in white ♀ & T2D, HR 0.76, 95% CI: 0.60, 0.96; Paleo 20-y high-score maintainers & T2D, per SD: HR 0.59, 95% CI: 0.39, 0.88. No interactions: race, sex, BMI and family history of T2D.; - Funding: NHLBI
Hlaing-Hlaing, 2021^69^; Australia; Australian Longitudinal; Study on Women’s Health (AL-SWH), 1946-51 cohort; Analytic N=5350; Participant characteristics:; - Health: BMI ~25, mean across all tertiles of different DP scores; Free of non-communicable diseases at S3 (2001).; - Race and/or Ethnicity: NR (Australian; “nationally-representative”); - SEP: 60-71% have easy ability to manage income; 15-30% graduated college, 81 to 85% married across all DQ quantiles; more participants with higher DQ scores had university/higher degrees; Selection data: Women without history of diabetes, CHD, HT, asthma, cancer (except skin cancer) at S3 in 2001. | Age at Dietary Pattern: 40 to 50 y at baseline; Mediterranean Diet Score (MDS) [Trichopolou 2003]; Alternative HEI (AHEI)-2010 [Chiuve 2012]; Healthy Eating Index for Australian Adults-2013 (HEIFA-2013)[Roy 2016]; MDS: Positive: Vegetables; Legumes; Fruit, Nuts; Cereals; Fish; MUFA/SFA. Negative: Red and Processed Meat; Dairy Products. Neutral: Alcohol; AHEI-2010: Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol HEIFA-2013: Positive: Vegetables; Vegetable variety; Fruit; Fruit variety; Total Grains; Whole grains; Fat (PUFA foods, US oils, nuts, seeds). Negative: Saturated Fat; Added Sugars; Discretionary Foods (including processed meat). Moderate: Dairy and Dairy Alternatives; Meat and Meat Alternatives (not processed); Methods: Index/Score | Follow-up: ~15y (S3, 2001 to S8, 2013); [underlined: Risk of T2D]: MDS (Q1, HR: 1, ref) & T2D at S8; Q5, HR: 0.76, 95% CI: 0.48, 1.21; AHEI-2010 (Q1, HR: 1, ref) & T2D at S8; Q5, HR: 0.44, 95% CI: 0.29, 0.66; HEIFA-2013 (Q1, HR: 1, ref) & T2D at S8; Q5, HR: 0.76, 95% CI: 0.52, 1.10; Summary: Inverse: AHEI-2010 &; T2D; NS/Null: MDS & T2D; NS/Null: HEIFA-2013 & T2D | - Did not account for: Race/Ethnicity; Family history of diabetes; Anthropometry (treated as mediator); - Diet assessment: FFQ once (baseline), tested against 7d food record; - Outcomes: Self-report; - All female participants; - Funding: None
Hlaing-Hlaing, 2022^68^; Australia; Australian Longitudinal; Study on Women’s Health (AL-SWH), 1973-78 cohort; Analytic N=5214, S8 (6560, S4; 5905, S5; 5814, S6; 5268, S7); Participant characteristics:; - Health: Majority not taking prescribed meds (~72-75%); - Race and/or Ethnicity: NR (Australian; “nationallyrepresentative”); - SEP: Majority employed (~7688%); Education varied ~18-36% high school, 35-59% university degree; Selection data: Excluded those with pregnancy, T2D, CHD, HTN, asthma, or cancer or missing FFQ at S3 (baseline) | Age at Dietary Pattern: 27.6y, mean (25 to 30y @ S3); [underlined: Alternative HEI (AHEI)-2010] [Chiuve 2012], Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol; Methods: Index/Score | Follow-up: ~15y (S3, 2001 to S8, 2013); [underlined: Risk of T2D]: AHEI-2010 & T2D at; S4, OR: 0.9, 95% CI: 0.2, 4.0; S5, OR: 1.5, 95% CI: 0.5, 4.5; S6, OR: 0.8, 95% CI: 0.4, 1.6; S7, OR: 0.7, 95% CI: 0.3, 1.4; S8, OR: 0.6, 95% CI: 0.3, 1.3; Summary: NS/Null: AHEI-2010 & T2D at S4, S5, S6, S7, or S8 | - Did not account for: Race/Ethnicity, Smoking, Family history of diabetes, Anthropometry; - Diet assessment: FFQ once (baseline), tested against 7d food record; - Outcomes: Self-report at each F/U survey; - All female participants;; - Funding: None
Hodge, 2021^70^; Australia; Melbourne Collaborative Cohort Study; Analytic N=25,888; Participant characteristics:; - Health: 43% OW (BMI 25–29.9), 20% Ob (BMI 30+); 35% high-WHR; 42% smoker (ever/any); 55% comorbidity; - Race and/or Ethnicity: NR; 69.8% born in Australia, 23.8% of southern European origin, 6.5% of northern European origin.; - SEP: SEIFA, Q1: 18%, Q5: 27%; Lower AHEI-2010 & MDS aherence associated with greater disadvantage (SEIFA, Socio-Economic Indexes for Areas); Selection data: Excluded those with diabetes at baseline or wave 1 f/u; those with missing demographic, anthropometric, or dietary data; those who died between baseline and wave 2 f/u | Age at Dietary Pattern: 55.2 y, mean; Alternative HEI (AHEI)-2010 [Chiuve 2012]; Mediterranean Diet Score (MDS) [Trichopolou 2003]; [underlined: AHEI-2010:] Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol; [underlined: MDS]: Positive: Vegetables; Legumes; Fruit, Nuts; Cereals; Fish; MUFA/SFA. Negative: Red and Processed Meat; Dairy Products. Neutral: Alcohol; Methods: Index/Score | Follow-up: ~4 y; [underlined: Risk of T2D]: AHEI-2010 & Incident; T2D, Q1, IRR: 1, ref; Q2, IRR: 0.98, 95% CI: 0.87, 1.11; Q3, IRR: 0.94, 95% CI: 0.83, 1.07; Q4, IRR: 0.91, 95% CI: 0.80, 1.04; Q5, IRR: 0.73, 95% CI: 0.63, 0.85; p-trend<0.001; MDS & Incident T2D, T1, IRR: 1, ref; T2, IRR: 0.94, 95% CI: 0.86, 1.03; T3, IRR: 0.98, 95% CI: 0.85, 1.13; p-trend=0.37; Summary: Inverse: AHEI-2010 & T2D; NS/Null (Inverse): MDS & T2D | - Did not account for: Race/Ethnicity (NR; adj. birth country); TEI; - Diet assessment: FFQ once (baseline); - Outcomes: Self-report at 2 surveys; - In analyses stratified by region of birth, inverse relationship between AHEI-2010 & T2D significant only for those from Australia & NZ; null for Northern Europe & Southern Europe. Inverse relationship between MDS & T2D for Austrialia & NZ (p=0.011), remained null for Northern Europe & Southern Europe. Mediation: 43% of effect between AHEI-2010 & T2D was explained by a substantial indirect effect through WHR, 35% of effect was explained by a substantial indirect effect through BMI.; - Funding: VicHealth, Cancer Council Victoria, Australian National Health and Medical Research Council
Jacobs, 2015^71^; USA; Multiethnic Cohort, MEC; Analytic N=89,185 total: Men: 41,918; Women: 47,267; Participant characteristics:; - Health: In men, by HEI C1; C3; C5; - BMI, kg/m2: 25.3 ± 5.0; 25.2 ± 4.5; 24.5 ± 4.2; - PA, h/wk: 1.6 ± 0.4; 1.7 ± 0.3; 1.7 ± 0.3; - Smoking, never smoker: 23.2%; 31.8%; 47.1%; - No regular soda consumption: 22.6%; 31.9%; 51.5%; - Alcohol intake<1 drink/mo: 38.3%; 37.1%; 38.5%; - In ♀ by HEI C1; C3; C5; - BMI, kg/m2: 24.1 ± 6.3; 23.5 ± 5.5; 22.7 ± 4.8; - PA, h/wk: 1.6 ± 0.4; 1.6 ± 0.3; 1.6 ± 0.3; - Smoking, never smoker: 47.9%; 58.3%; 62.7%; - No regular soda consumption: 32.3%; 48.1%; 64.0%; - Alcohol intake<1 drink/month: 66.1%; 64%; 63.5%; - Race and/or Ethnicity: 12.9% (11–25%) Hawaiian-American; 42.3% (12–25%) Japanese-American; 35.7% (11–32%) White; 9.1% Other ancestry; respective mixed ethnic backgrounds: 3%, 5%, and 84% for Japanese-American, white and Native; - Hawaiian participants; of Native Hawaiian: 29% Haw; - SEP: Education (college graduates); - men: 29- 44%; - ♀: 25–36%; Selection data: Excluded those w/ diabetes at entry, questionable diabetes status, invalid/missing convariate data | Age at Dietary Pattern: 45 to 75 y; Healthy Eating Index (HEI-2010) [Guenther 2013]; Alternative HEI (AHEI)-2010 [Chiuve 2012]; Alternate Mediterranean Diet Score (aMED) [Fung 2005]; Dietary Approaches to Stop; Hypertension (DASH) [Fung 2008]:; HEI-2010: Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; Fatty Acids. Negative: Refined Grains; Added Sugars in “Empty Calories”; Solid Fats in “Empty Calories”; Sodium; AHEI-2010: Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol aMED: Positive: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA/SFA. Negative: Red and Processed Meat. Neutral: Alcohol; DASH: Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Sodium; Methods: Index/Score | Follow-up: NR, inferred: 3–14y, T2D; [underlined: Risk of T2D]:; Men, C1, HR: 1, ref; HEI-2010; C2, HR: 1.00, 95% CI: 0.93, 1.08; C3, HR: 0.99, 95% CI: 0.92, 1.08; C4, HR: 0.94, 95% CI: 0.87, 1.03; C5, HR: 0.93, 95% CI: 0.85, 1.01; Per SD, HR: 0.97, 95% CI: 0.94, 1.00; AHEI-2010; C2, HR: 1.00, 95% CI: 0.92, 1.08; C3, HR: 0.93, 95% CI: 0.86, 1.01; C4, HR: 0.90, 95% CI: 0.83, 0.98; C5, HR: 0.88, 95% CI: 0.81, 0.96; Per SD, HR: 0.95, 95% CI: 0.92, 0.97; aMED; C2, HR: 0.99, 95% CI: 0.91, 1.08; C3, HR: 0.92, 95% CI: 0.84, 1.00; C4, HR: 0.87, 95% CI: 0.80, 0.95; C5, HR: 0.89, 95% CI: 0.80, 0.99; Per SD, HR: 0.95, 95% CI: 0.92, 0.98; DASH; C2, HR: 0.91, 95% CI: 0.84, 0.98; C3, HR: 0.91, 95% CI: 0.85, 0.99; C4, HR: 0.86, 95% CI: 0.78, 0.94; C5, HR: 0.79, 95% CI: 0.73, 0.87; Per SD, HR: 0.93, 95% CI: 0.90, 0.96; Women, C1, HR: 1, ref; HEI-2010; C2, HR: 1.01, 95% CI: 0.93, 1.09; C3, HR: 0.91, 95% CI: 0.84, 0.99; C4, HR: 0.93, 95% CI: 0.85, 1.01; C5, HR: 0.92, 95% CI: 0.84, 1.01; Per SD, HR: 0.97, 95% CI: 0.95, 1.00; AHEI-2010; C2, HR: 1.01, 95% CI: 0.93, 1.09; C3, HR: 0.99, 95% CI: 0.91, 1.08; C4, HR: 0.96, 95% CI: 0.88, 1.05; C5, HR: 0.88, 95% CI: 0.80, 0.97; Per SD, HR: 0.95, 95% CI: 0.92, 0.98; aMED; C2, HR: 0.95, 95% CI: 0.87, 1.04; C3, HR: 1.02, 95% CI: 0.93, 1.11; C4, HR: 0.96, 95% CI: 0.88, 1.06; C5, HR: 0.92, 95% CI: 0.84, 1.02; Per SD, HR: 0.97, 95% CI: 0.94, 1.00; DASH; C2, HR: 0.91, 95% CI: 0.84, 0.98; C3, HR: 0.85, 95% CI: 0.79, 0.93; C4, HR: 0.82, 95% CI: 0.75, 0.90; C5, HR: 0.77, 95% CI: 0.70, 0.84; Per SD, HR: 0.91, 95% CI: 0.88, 0.94; Summary: NS/Null: HEI-2010 & T2D; (♀ or ♂); aMED & T2D ♀; Inverse: AHEI-2010 & T2D (♀ or ♂); aMED & T2D ♂; DASH & T2D (♀ or ♂) | - Did not account for: Family history of diabetes; - Diet assessment: FFQ once (baseline; ethnic specific); - Outcomes: Self-report, verified by registry; - Some missing data on T2D diagnosis; Subtraction of empty calories [alcohol+SoFAS] from HEI B=−0.11, PEE −83%; alcohol from aMED B=−0.01 PEE: −40% all men; alcohol from aHEI, B=−0.05, PEE 0%; - Funding: NCI; NIH;
Jacobs, 2017^(a priori)72^; USA; Multiethnic Cohort, MEC; Analytic N=166,550 (total): Men, 74,693; Women, 91,857; 10,060 (biomarker subcohort) Men, 4661; Women, 5399; Participant characteristics:; - Health: mean BMI, kg/m2: ~ 26.4–26.6; - Race and/or Ethnicity: African American: 16.3%; - Japanese American: 26.4%; - Latino: 22.0%; - Native Hawaiian: 6.5%; - White: 22.9%; - Other ancestry: 5.8%; - SEP: Education ≤12 y: 41–45%; 13–15 y: 29–30%; ≥16 y: 14–18%; Selection data: Excluded participants who reported T2D at cohort entry, members of other ethnicity and individuals with missing values for essential covariates (for biomarkers: additionally prevalent T2D at blood draw and missing biomarker information) | Age at Dietary Pattern: 45 to 75 y; [underlined: Healthy Eating Index (HEI-2010) [Guenther 2013]], Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; Fatty Acids. Negative: Refined Grains; Added Sugars in “Empty Calories”; Solid Fats in “Empty Calories”; Sodium; [underlined: Alternative HEI (AHEI)-2010] [Chiuve 2012]: Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol; [underlined: Alternate Mediterranean Diet Score(aMED) [Fung 2005]:] Positive: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA/SFA. Negative: Red and Processed Meat. Neutral: Alcohol; [underlined: Dietary Approaches to Stop Hypertension (DASH) score [Fung2008]], Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Sodium; Methods: Index/Score | Follow-up: 14.8 y median, T2D; [underlined: Risk of T2D]: In men, T3 v. T1 (ref); HEI-2010; All, HR: 0.93, 95% CI: 0.86, 1.00; White, HR: 0.92, 95% CI: 0.78, 1.09; African American (Am.), HR: 0.99, 95% CI: 0.79, 1.24; Native Am., HR: 0.93, 95% CI:0.72, 1.20; Japanese Am., HR: 0.97, 95% CI: 0.84, 1.11; Latino, HR: 0.91, 95% CI: 0.77, 1.06; AHEI-2010; All, HR: 0.85, 95% CI: 0.79, 0.92; White, HR: 0.90, 95% CI: 0.76, 1.05; African Am., HR: 0.75, 95% CI: 0.59, 0.96; Native Am., HR: 0.82, 95% CI: 0.64, 1.06; Japanese Am., HR: 0.90, 95% CI: 0.79, 1.03; Latino, HR: 0.85, 95% CI: 0.72, 1.00; aMED; All, HR: 0.85, 95% CI: 0.77, 0.92; White, HR: 0.88, 95% CI: 0.73, 1.05; African Am., HR: 0.85, 95% CI: 0.64, 1.11; Native Am.: HR 0.81, 95% CI:0.60, 1.08; Japanese Am., HR: 0.83, 95% CI: 0.71, 0.96; Latino, HR: 0.91, 95% CI: 0.76, 1.09; DASH; All, HR: 0.81, 95% CI: 0.75, 0.88; White, HR: 0.74, 95% CI: 0.62, 0.88; African Am., HR: 0.79, 95% CI: 0.63, 1.00; Native Am., HR: 0.87, 95% CI: 0.67, 1.12; Japanese Am., HR: 0.89, 95% CI: 0.78, 1.02; Latino, HR: 0.82, 95% CI: 0.70, 0.97; In ♀ T3 v. T1 (ref); HEI-2010; All, HR: 0.93, 95% CI: 0.86, 1.00; White, HR: 0.82, 95% CI: 0.69, 0.98; African Am., HR: 0.90, 95% CI: 0.76, 1.06; Native Am., HR: 1.03, 95% CI: 0.83, 1.29; Japanese Am., HR: 1.03, 95% CI: 0.90, 1.18; Latino, HR: 0.90, 95% CI: 0.76, 1.07; AHEI-2010; All, HR: 0.90, 95% CI: 0.83, 0.97; White, HR: 0.80, 95% CI: 0.67, 0.95; African Am., HR: 0.89, 95% CI: 0.75, 1.06; Native Am., HR: 0.88, 95% CI: 0.71, 1.10; Japanese Am., HR: 0.96, 95% CI: 0.83, 1.11; Latino, HR: 0.98, 95% CI: 0.83, 1.15; aMED; All, HR: 0.93, 95% CI: 0.86, 1.00; White, HR: 0.89, 95% CI: 0.74, 1.06; African Am., HR: 0.86, 95% CI: 0.72, 1.02; Native Am., HR: 1.01, 95% CI: 0.80, 1.28; Japanese Am. HR: 1.04, 95% CI: 0.90, 1.20; Latino, HR: 0.90, 95% C,I: 0.77, 1.06; DASH; All, HR: 0.80, 95% CI: 0.73, 0.86; White, HR: 0.68, 95% CI: 0.56, 0.83; African Am., HR: 0.85, 95% CI: 0.70, 1.02; Native Am., HR: 0.88, 95% CI: 0.68, 1.13; Japanese Am., HR: 0.85, 95% CI: 0.73, 0.99; Latino, HR: 0.84, 95% CI: 0.70, 1.00; [underlined: HOMA-IR:] in Men; HEI-2010 (geometric mean, GM); T1: GM=1.55, 95% CI: 1.49, 1.60; T2: GM=1.46, 95% CI: 1.41, 1.51; T3: GM=1.43, 95% CI: 1.38, 1.48; P for trend=0.004; AHEI-2010; T1: GM=1.55, 95% CI: 1.50, 1.60; T2: GM=1.47, 95% CI: 1.43, 1.52; T3: GM=1.43, 95% CI: 1.39, 1.48; P for trend=0.002; aMED; T1: GM=1.50, 95% CI: 1.45, 1.56; T2: GM=1.50, 95% CI: 1.45, 1.54; T3: GM=1.44, 95% CI: 1.38, 1.50; P for trend=0.15; DASH; T1: GM=1.54, 95% CI: 1.49, 1.59; T2: GM=1.46, 95% CI: 1.41, 1.51; T3: GM=1.45, 95% CI: 1.40, 1.50; P for trend=0.02; Summary: Inverse, NS: Higher HEI-2010 & Lower T2D in all ♂, and ♀, White, African-American, Native Hawaiian, Japanese American, Latino ♂, African American and Latino ♀; Inverse, NS: Higher AHEI-2010 & Lower T2D in white ♂ and African American ♀, Native Hawaiian, Japanese American, Latino ♂ and ♀; Inverse, NS: Higher aMED & Lower T2D in all ♀, White, African American, Latino ♂ and ♀, and Native Hawaiian ♂; Inverse, NS: Higher DASH & African American, Native Hawaiian ♂ and ♀, Japanese American ♂, and Latino ♀; Inverse, NS: Higher AHEI-2010 & Lower HOMA-IR in ♂; HEI-2010, aMED & HOMA-IR in ♀; Inverse: Higher AHEI-2010, DASH & Lower T2D in all ♂ and ♀; Inverse: Higher aMED & Lower T2D in all ♂; Inverse: Higher HEI-2010 & Lower T2D in White ♀; Inverse: Higher AHEI-2010 & Lower T2D in African American ♂, White ♀; Inverse: Higher aMED & Lower T2D in Japanese American; Inverse: Higher DASH & Lower T2D in White ♂ and ♀, Latino ♂ and Japanese American ♀; Inverse: Higher HEI-2010, aMED, DASH & Lower HOMA-IR in ♂; Inverse: Higher HEI-2010, AHEI-2010, DASH & HOMA-IR in ♀; Positive, NS: Higher HEI-2010, aMED & Higher T2D in Native Hawaiian, Japanese American | - Did not account for: Alcohol (not for HEI-2010, DASH); Family history of diabetes; - Diet assessment: FFQ once (baseline; ethnic specific); - Outcomes: Self-report 3x, confirmed with data [false-positive self-reports without confirmation were excluded]; - Biomarker subcohort was relatively small sample size from full MEC; - Funding: NCI;NIH; German Research Foundation
Jacobs, 2017^(Dietary)^ ^73^; USA; Multiethnic Cohort, MEC; Analytic N=10,008 (boimarker); 155,316 (T2D); Participant characteristics (males; females):; Health:; - BMI, kg/m2: 26.6 ± 4.2; 26.5 ± 5.8; - PA <30 min/d: 36%; 44%; - Smoking status, Never: 30%; 57%, Past: 52%; 29%; Race and/or Ethnicity; - White: 23.7%; 22.4%; - African American: 13.2%; 18.7%; - Native Hawaiian: 6.5%; 6.9%; - Japanese American: 27.8%; 25.3%; - Latinos: 11.5%; 10% SEP:; - Males: Education ≤12 y: 42.3%; 13–15 y: 28.8%; ≥16 y: 28.9%; - Females: Education ≤12 y: 46.8%; 13–15 y: 28.8%; ≥16 y: 24.4%; - Selection data: Excluded T2D cases with diagnosis before or at blood draw, ethnicities/races other than the 5 major groups, incomplete main confounder information, and incomplete or implausible biomarker information for RRR. Excluded biomarker subcohort, prevalent diabetes cases at entry, minority ethnic groups, and those with missing information on essential covariate were excluded for these analyses. | Age at Dietary Pattern: 45 to 75 y; [underlined: For all ethnicities combined], Positive: whole grains, fruit, yellow-orange vegetables, green vegetables, low-fat dairy; Negative: processed and red meat, sugar-sweetenend beverages, diet soft drinks, and white rice; [underlined: African Americans], Positive: yellow-orange vegetables, cruciferous vegetables, green vegetables, tomatoes, low-fat dairy, whole grains; Negative: processed meat, red meat, poultry, shellfish, other potatoes and tubers; [underlined: Japanese Americans], Positive: green vegetables, yellow-orange vegetables, legumes, fruit, low-fat dairy, whole grains; Negative: processed meat, red meat, eggs, white rice; [underlined: Latino], Positive: fish, green vegetables, yellow-orange vegetables, fruit, nuts, low-fat dairy, whole grains; Negative: processed meat, red meat, sugar-sweetened beverages; [underlined: Native Hawaiians,] Positive: coffee, alcohol, nuts, cottage cheese; Negative: red meat, poultry, diet soft drinks, other potatoes and tubers, French-fried potatoes, white rice; [underlined: White,] Positive: legumes, cruciferous vegetables, green vegetables, other vegetables, fruit; Negative: red meat, white rice, sugar-sweetened beverages; Methods: RRR | Follow-up: 14.8y (mean); 9.5 [2.2] y mean, biomarker; [underlined: Risk of T2D]: RRRDS com, in all participants, T1, HR: 1, ref; T2, HR: 0.87, 95% CI: 0.83, 0.92; T3, HR: 0.79, 95% CI: 0.75, 0.84; Per unit z-standardized, HR: 0.91, 95%; CI: 0.89, 0.93; In African American; T2, HR: 0.92, 95% CI: 0.81, 1.05; T3, HR: 0.81, 95% CI: 0.70, 0.94; Per unit z-standardized, HR: 0.93, 95%; CI: 0.87, 0.99; In Japanese American; T2, HR: 0.88, 95% CI: 0.80, 0.96; T3, HR: 0.84, 95% CI: 0.76, 0.93; Per unit z-standardized, HR: 0.93, 95%; CI: 0.89, 0.97; In Latino; T2, HR: 0.94, 95% CI: 0.84, 1.05; T3, HR: 0.81, 95% CI: 0.72, 0.92; Per unit z-standardized, HR: 0.89, 95%; CI: 0.85, 0.93; In Native Hawaiian; T2, HR: 0.84, 95% CI: 0.71, 1.00; T3, HR: 0.83, 95% CI: 0.71, 0.99; Per unit z-standardized, HR: 0.95, 95%; CI: 0.89, 1.00; In White; T2, HR: 0.83, 95% CI: 0.74, 0.93; T3, HR: 0.72, 95% CI: 0.63, 0.81; Per unit z-standardized, HR: 0.87, 95%; CI: 0.83, 0.92 With RRRDSethni (derived within each ethnicity); In African American; T2: HR 0.99, 95% CI: 0.87, 1.13; T3: HR 0.84, 95% CI: 0.73, 0.96; Per unit Z-standardized: HR 0.93, 95%; CI: 0.88, 0.99; In Japanese American; T2: HR 0.88, 95% CI: 0.80, 0.96; T3: HR 0.82, 95% CI: 0.74, 0.91; Per unit Z-standardized: HR 0.92, 95%; CI: 0.88, 0.96; In Latino; T2: HR 0.89, 95% CI: 0.80, 1.00; T3: HR 0.83, 95% CI: 0.74, 0.94; Per unit Z-standardized: HR 0.92, 95%; CI: 0.88, 0.97; In Native Hawaiian; T2: HR 0.90, 95% CI: 0.77, 1.05; T3: HR 0.69, 95% CI: 0.57, 0.82; Per unit Z-standardized: HR 0.89, 95%; CI: 0.84, 0.95; In White; T2: HR 0.81, 95% CI: 0.72, 0.91; T3: HR 0.76, 95% CI: 0.67, 0.86; Per unit Z-standardized: HR 0.89, 95%; CI: 0.85, 0.93; Summary: Inverse: Higher RRRDScomb & Lower T2D in all participants, African American, Japanese American, Latino, Native Hawaiian and White subgroups; Higher RRRDSethni & Lower T2D in each ethnicity subgroup | - Did not account for: Alcohol; Family history of diabetes; - Diet assessment: FFQ once (baseline; ethnic specific); - Outcomes: Self-report, confirmed with registry etc. False-positive were excluded; - Sensitivity analyses by excluding participants with lipid-lowering and anti-inflammatory medication use, non-fasting participants, participants with acute inflammation, or with extreme energy intakes yielded similar results in RRR analysis; participants who provided blood yielded similar results in the Cox regression.; - Funding: German Research Foundation; NIH;
Jannasch, 2019^74^; Europe: Denmark, France, Germany, Italy, the Netherlands, Spain, Sweden; UK; EPIC-InterAct; Analytic N=25,158 total: Subcohort: 14,694; T2D cases: 11,183; Participant characteristics:; - Health: BMI, kg/m2: 26.1 ± 4.2 (mean in total cohort); - WC, cm, ♂: 95.2 ± 10.0; ♀: 81.2 ± 11.2; - Physically active: 20.2%; - Never smoking: 45.9%; - Family history of diabetes: 19.2%; - HbA1c ≥ 6.5%: 1.6%; - Race and/or Ethnicity: NR; % in subcohort v. whole case-cohort from France: 3.8% v. 3.3%; Italy: 13.1% v. 12.7%; Spain: 23.9% v. 22.9%; UK-Norfolk: 6.1% v. 6.4%; UK-Oxford: 2.15% v. 2.1%; Netherlands: 9.5% v. 8.4%; Germany: 13.9% v. 14.1%; Sweden: 13.1% v. 14.1%; Denmark: 14.4%; - SEP: Post-secondary education, %:; - France: 39.9%; - Italy: 14.5%; - Spain: 11.3%; - UK-Norfolk: 12.3%; - UK-Oxford: 42.4%; - Netherlands: 21.7%; - Germany: 34.9%; - Sweden: 22.4%; - Denmark: 20.4%; - Selection data: For subcohort, randomly selected from participants who had stored blood samples and reported dieabetes status, excluded prevalent diabetes, postcensoring diabetes, and individuals with unkown status, participants from Swedish study center Umea, data missing on diet, anthropometry, and lifestyle factors;; - Included data on ascertained T2D, excluded prevalent and postcensoring diabetes, unknown status, self-reported diabetes in Denmark, nondiabetic participants, data from UMEA, missing data on diet, anthropometry, and lifestyle factors. | Age at Dietary Pattern: 52.9 y, mean (enrolled 35 to 70 y); France DP1: Positive: leafy vegetables, fruiting vegetables, root vegetables, cabbage, red meat, poultry. Negative: other vegetables; France DP2: Positive: nuts, other fruits, processed meat, fish, eggs, cake and cookies, coffee, and other alcoholic beverages; Italy DP1: Positive: leafy vegetables, fruiting vegetables, cabbage, other vegetables, legumes, fish, vegetable oils; Italy DP2: Positive: pasta & rice, red meat, processed meat, other fats, sugar; Spain DP1: Positive: potatoes, legumes, bread, red meat, processed meat, eggs, vegetable oils, wine and spirits; Spain DP2: Positive: leafy vegetables, fruiting vegetables, root vegetables, other vegetables, other fruits; UK-Norfolk DP1: Positive: leafy vegetables, fruiting vegetables, root vegetables, cabbage, other vegetables, fruits, pasta & rice; UK-Norfolk DP2: Positive: potatoes, processed meat, vegetable oils, sugar, cakes and cookies, and tea; UK-Oxford DP1: Positive: leafy vegetables, fruiting vegetables, root vegetables, cabbage, other vegetables, legumes, fruits; UK-Oxford DP2: Positive: potatoes, red meat, poultry, processed meat, offals, fish, vegetable oils; Netherlands DP1: Positive: potatoes, bread, red meat, processed meat, margarine, other fats, sugar; Netherlands DP2: Positive: fruiting vegetables, other fruits, pasta & rice, other cereals, poultry, vegetable oils, other fats; Germany DP1: Positive: leafy vegetables, fruiting vegetables, root vegetables, other vegetables, fruits, vegetable oils; Germany DP2: Positive: potatoes, red meat, poultry, processed meat, offals, other fats, beer; Sweden DP1: Positive: potatoes, bread, processed meat, margarine, sugar. Negative: other non-alcoholic beverages; Sweden DP2: Positive: wine, other alcoholic beverages (no other groups met 0.4 factor loading cutoff); Denmark DP1: Positive: leafy vegetables, fruiting vegetables, root vegetables, cabbage, other vegetables, legumes, fruits, pasta & rice, poultry, fish, vegetable oils; Denmark DP2: Positive: potatoes, bread, red meat, processed meat, offals, margarine; Methods: Factor or cluster analysis | Follow-up: 6.9 y mean, T2D; [underlined: Risk of T2D]: DP1 in France, HR: 1.06, 95% CI: 0.90, 1.26, p-trend=0.49 DP2 in France, HR: 0.64, 95% CI: 0.49, 0.85, p-trend=0.002; “Replicative France”, all, per SD: HR 1.00, 95% CI: 0.90, 1.10; DP1 in Italy, HR: 1.10, 95% CI: 0.98, 1.23, p-trend=0.10; DP2 in Italy, HR: 1.01, 95% CI: 0.89, 1.14, p-trend=0.93; DP1 in Spain, HR: 1.14, 95% CI: 1.03, 1.27, p-trend=0.02; DP2 in Spain, HR: 1.02, 95% CI: 0.95, 1.09, p-trend=0.67; “Simple Spain” score, all, per SD: HR 1.09, 95% CI: 0.97, 1.22; DP1 in UK-Norfolk, HR: 0.89, 95% CI: 0.77, 1.03, p-trend=0.11; DP2 in UK-Norfolk, HR: 1.24, 95% CI: 1.02,1.51, P=0.03; “Replicative Norfolk”, all, perSD: HR 1.12, 95% CI: 1.04, 1.20; DP1 in UK-Oxford, HR: 1.11, 95% CI: 0.88, 1.39, p-trend=0.38; DP2 in UK-Oxford, HR:1.22, 95% CI: 0.94, 1.60, p-trend=0.14; DP1 in Netherlands, HR: 1.10, 95% CI: 0.93, 1.29, p-trend=0.27; DP2 in Netherlands, HR: 0.92, 95% CI: 0.79, 1.06, p-trend=0.24; DP1 in Germany, HR: 0.97, 95% CI: 0.88, 1.07, p-trend=0.55; DP2 in Germany, HR: 1.08, 95% CI: 0.96, 1.21, p-trend=0.19; DP1 in Sweden, HR: 1.08, 95% CI: 0.95, 1.23, p-trend=0.25; DP2 in Sweden, HR: 1.00, 95% CI: 0.91, 1.09, p-trend=0.91; DP1 in Denmark, HR: 0.98, 95% CI: 0.90, 1.06, p-trend=0.60; DP2 in Denmark, HR: 1.08, 95% CI: 0.94, 1.24, p-trend=0.26; Summary:; Inverse: France DP2 & T2D; “Replicative France” & T2D in France;; Positive: Spain DP1, UK-Norfolk DP2 & Higher T2D; “Replicative Norfolk” & T2D (in all participants); “Replicative France” & T2D in UK Norfolk; “Simple Spain” & T2D in Spain or UK Norfolk; NS/Null: “Replicative France”, “Simple Spain” & T2D in all participants; all other country-specific DPs & T2D within that country | - Did not account for: Race and/or ethnicity,; - Alcohol (only Norfolk DP); - Diet assessment: Questionnaires once (country/centre-specific); - Outcomes: Combination of selfreport, linkage to registries, hospital/mortality data; - Excluding participants in the top and bottom 1% of TEI, w/ CVD at baseline, incident T2D in first 2 y F/U, or HbA1c values ≥6.5%, or adjusting for Family history of T2D did not alter the results.; - Funding: European Union Sixth Framework Programme; German Federal Ministry of Education and Research; Determinants of Diet and Physical Activity (DEDIPAC); “Healthy Diet for a Healthy Life”; NutriAct-Competence Cluster Nutrition Research Berlin-Potsdam; Associazio
Jin, 2021^75^; USA; Women Health Initiative (WHI); Analytic N=73,495; Participant characteristics:; - Health: Those without T2D, cancer, CVD at baseline; - Race and/or Ethnicity: EDIH; - Q1: 3.5% African American, 0.2% American Indian or Alaskan Native, 2.4% Hispanic American, 2.1% Asianor Pacific Islander, 90% European American, 1.5% Other; - Q3, 5.3% African American, 0.4% American Indian or Alaskan Native, 3.3% Hispanic American, 3.3; - SEP: Majority had ≥4 y college;; - EDIH, Education: 1–2% ≤ 8 y, 3–6% some high school/high school/GED, 20–34% some college/associate degree, 57–76% ≥4 y college; - EDIP, Education: 1–4% ≤ 8 y, 3–6% some high school/high school/GED, 23–32% some college/associate degree, 58–73% ≥4 y college; Selection data: Women only; Excluded those with T2D, CVD, or prevalent cancer (except nonmelanoma skin cancer) at baseline; implausible energy intake (<600 kcal/day and >5,000 kcal/day); extreme BMI (<15 or >50 kg/m2); no T2D status; those in the Dietary Modification Trial | Age at Dietary Pattern: 50 to 79 y at baseline; [underlined: Empirical dietary inflammatory pattern(EDIP) [Tabung, 2016],] Anti-inflammatory group: tea, coffee, dark yellow vegetables (carrots, or squash), leafy green vegetables (cabbage, spinach, or lettuce), snacks (cracker, or potato chips), fruit juice (apple juice, cantaloupe juice, orange juice, or other fruit juice), pizza. Pro-inflammatory group: processed meat (sausage), red meat (beef, or lamb), organ meat (beef, calf, or chicken liver), other fish (canned tuna, or fish), other vegetables (mixed vegetables, green pepper, cooked mushroom, eggplant, zucchini, or cucumber), refined grains (white bread, biscuit, white rice, pasta, or vermicelli), high-energy and low energy beverages (cola with sugar, carbonated beverages with sugar, fruit punch drinks), and tomatoes; [underlined: Empirical dietary index forhyperinsulinemia (EDIH) [Tabung,2016],] Positive: Red meat; Processed meat; Poultry; Tomatoes; French fries, Fish (other than dark-meat fish); Low-fat dairy; Eggs; High-energy beverages (cola and other carbonated beverages with sugar, fruit drinks); Low-energy beverages; Margarine; Cream soups; Negative: Green leafy vegetables; Whole fruit; High-fat dairy products; Coffee; Wine; Methods: Index/Score | Follow-up: 13.3 y (median); [underlined: Risk of T2D]: Incident T2D - EDIH; Q1, HR: 1, ref; Q2, HR: 1.15, 95% CI: 0.96, 1.37; Q3, HR: 1.02, 95% CI: 0.86, 1.21; Q4, HR: 1.17, 95% CI: 0.99, 1.38; Q5, HR: 1.41, 95% CI: 1.20, 1.65 per 1-SD, HR: 1.12, 95% CI: 1.07, 1.17; p-trend<0.0001; Incident T2D - EDIP; Q1, HR: 1, ref; Q2, HR: 1.00, 95% CI: 0.85, 1.18; Q3, HR: 1.08, 95% CI: 0.92, 1.27; Q4, HR: 1.27, 95% CI: 1.09, 1.49; Q5, HR: 1.42, 95% CI: 1.22, 1.65 per 1-SD, HR: 1.14, 95% CI: 1.09, 1.19; p-trend<0.0001; Summary: Positive: EDIH, EDIP & T2D | - Did not account for: N/A (all); - Diet assessment: FFQ once (baseline); - Outcomes: Self-report of T2D incidence from use of T2D-meds, not including Tx via lifestyle; - EDIP & T2D still significant when controlling for baseline blood glucose levels; EDIH & T2D no longer significant when controlling for baseline blood glucose levels; - Funding: NIH
Kanerva, 2014^76^; Finland; Helsinki Birth Cohort Study; Health 2000 Survey; Analytic N=1822, HBCS 4923, Health 2000; Participant characteristics:; - Health: HBCS cohort, range by BSDS quintiles:; - Exercise <1 times/week: 7–20%; - Current smoker: 10–41%; - Abdominal obesity: 36–50%; - Elevated fasting glucose: 35–43%; - Hypertriglyceridemia: 18–32%; - Decreased HDL-C: 7–11%; - HTN: 83–85%; - Health 2000 cohort, range by BSDS quintiles:; - Exercise <1 times/week: 11–35%; - Current smoker: 17–37%; - Abdominal obesity: 34–38%; - Elevated fasting glucose: 23–24%; - Hypertriglyceridemia: 27–31%; - Decreased HDL-C: 30–32%; - HTN: 61- 63%; - Race and/or Ethnicity: NR (Finnish); - SEP: Education: HBCS cohort 11 to 13y; Health 2000 cohort: 11 to 12y; Selection data: Included participants who filled in FFQ and were free of T2D at baseline; | Age at Dietary Pattern: 62 y, mean in HBCS; 47 to 55 y, mean in Health 2000; Baltic Sea Diet Score (BSD) [Kanerva, 2013], Positive: Vegetables (including legumes, not potatoes); Apples/pears/peaches plus berries; Cereals; Low- and non-fat Milk; Fatty fish; E% from fat PUFA/SFA & Trans FA; Negative: Red and Processed Meat; Total Fat; Total Energy; Neutral: Total alcohol; Methods: Index/Score | Follow-up: 9.4 y median, HBCS cohort; 11.3 y median, Health 2000; [underlined: Risk of T2D]: BSD, Q1, HR: 1, ref; Q2, HR: 0.89, 95% CI: 0.63, 1.27; Q3, HR: 0.81, 95% CI: 0.62, 1.05; Q4, HR: 0.89, 95% CI: 0.69, 1.14; Q5, HR: 0.93, 95% CI: 0.72, 1.21; P for trend=0.53; Summary: Null: BSDS & T2D | - Did not account for: Race and/or ethnicity, Family history of diabetes; - Diet assessment: FFQ once (baseline); - Outcomes: National registries; - Interaction with MetHealth was not significant; risk increased non-significantly among Met disregulations>2, and decreased non-significantly among Met disregulations<2;; - Sensitivity analyses by excluding the first 2y F/U, under-reporters of energy intake, participants with elevated fasting glucose, including only participants with T2D confirmed with OGTT in the HBCS did show different results; Potential pre-baseline diet change for baseline metabolic dysregulation; underestimates of T2D; under or overreporting diet; Logistic regression for HR? did not mention about time scale - not sure how valid this analytical method is); - Funding: Stockman Foundation, Juho Vainio Foundation and the Yrjo Ja/hnsson Foundation; the Academy of Finland; the Finnish Diabetes Research Society, Folkha¨ lsan Research Foundation, Novo Nordisk; - Foundation, Finska La¨karesa¨ llskapet, Liv and Ha¨ lsa, Samfundet
Kesse-Guyot, 2021^77^; France; NutriNet-Santé Cohort; Analytic N=79205; Participant characteristics:; - Health: range from PNNS-GS2 quintiles; - BMI, kg/m2: 22.83 ± 3.80 to 24.45 ± 5.04; - Alcohol use, g/d: 3.83 ± 5.49 to 14.08 ± 16.59; - Physical activity ≥ 60 min/d: 27–35%; - Smoking, non-smokers: 44–55%; - Family history of diabetes: 15–17%; - Race and/or Ethnicity: NR (French); - SEP: Education, university: 62–66%; - Occupation, self-employed: 2%, managerial: 22–25%, employees: 15–23%, professions: 17–18%, retired: 13–24%; - Income, ≤1200 €/cu: 14–51%, 1200–1800 €/cu: 22–33%, 1800–2700 €/cu: 15–25%, > 2700 €/cu: 16–29%; - Living status, cohabiting: 70–74%; - Selection data: Included NutriNet-Sante participants with at least three completed 24-h records during the first 2 y, who were not detected as under or overreporters, and with available data about organic food consumption for computing the PNNS-GS2.; Excluded participants with no follow-up and prevalent cases of T2D. | Age at Dietary Pattern: 41.5 [14.5] y; [underlined: Programme National Nutrition Sante Guideline Score, updated for 2017 Guidelines in France (PNNS-GS2) [modified Estaquio 2009 by Chaltiel2019], mPNNS-GS2,] Positive: Fruits & vegetables (preferably organic); nuts; legumes (preferably organic); whole grain foods (preferably organic); fatty fish; milk and dairy products. Negative: Red meat; processed meat (prefer white ham over other processed meat); added fat (preferably vegetable fat over animal fat); sugary foods; sweettasting beverages; alcohol beverages; salt. Neutral: breads, cereals, potatoes; meat, poultry, other fish and seafood, and eggs; [underlined: SmPNNS-GS2,] Positive: nuts; milk and dairy products. Negative: sugary foods; sweet-tasting beverages; alcohol beverages; salt. Neutral: breads, cereals, potatoes; meat, poultry, seafood, and eggs; Methods: Index/Score | Follow-up: 6.8 [2.7] y mean, 7.4 y (4.2) median (IQR), T2D; [underlined: Risk of T2D]:; PNNS-GS2, Q1, HR: 1, ref; Q2, HR: 0.79, 95% CI: 0.63, 1.00; Q3, HR: 0.62, 95% CI: 0.47, 0.80; Q4, HR: 0.57, 95% CI: 0.43, 0.75; Q5, HR: 0.51, 95% CI: 0.37, 0.69; P-trend=0.0001; Per 1-point, HR: 0.92, 95% CI: 0.89, 0.94; sPNNS-GS2, Q1, HR: 1, ref; Q2, HR: 0.65, 95% CI: 0.51, 0.82; Q3, HR: 0.57, 95% CI: 0.44, 0.73; Q4, HR: 0.53, 95% CI: 0.40, 0.69; Q5, HR: 0.46, 95% CI: 0.35, 0.62; P-trend=0.0001; Per 1-point, HR: 0.92, 95% CI: 0.89, 0.95; Summary: Inverse: PNNS-GS2, sPNNS-GS2 & T2D | - Did not account for: Race and/or ethnicity; - Diet assessment: 24h recalls every 6mo (used average of 2.2 surveys); - Outcomes: Combination of self-report, medication use, reimbursement using Health insurance; - Sensitivity analysis showed similar results; the association was observed both ♂ and ♀;; - Limitations: observational study, limiting causal inference; participants are not representative of general French population; residual confounding; self-reported data;; - Funding: Ministere de la Sante, Sante Publique France, Institut National de la Sante et de la Recherche Medicale, Institut national de recherche pour l’agriculture, l’alimentation et l’environnement, Conservatoire National des Arts et Metiers
Khalili-Moghadam, 2019^78^; Iran; Tehran Lipid and Glucose Study (TLGS); Analytic N=2139; Participant characteristics:; - Health: range from MDS tertiles: HTN, 14.6 to 20.8%, p-trend=0.98; SBP, 109 ± 15.3 112 ± 17.8; p-trend=0.01; DBP, 72.6 ± 10.2 73.5 ± 10.7; p-trend=0.27; TG, 1.5 to 1.6; p-trend=0.03; HDL, 1.09 ± 0.26 1.13 ± 0.25; p-trend=0.06; - Race and/or Ethnicity: NR (Iranian); - SEP: NR; Selection data: Excluded those with incomplete dietary assessments; diabetes at baseline; unusual energy intake; no data on biochemical, anthropometry, physical activity; LFU | Age at Dietary Pattern: 20 to 70 y at baseline; [underlined: Mediterranean Diet Score (MDS) [Trichopolou 2003],] Positive: Vegetables; Legumes; Fruit, Nuts; Cereals; Fish; MUFA/SFA. Negative: Red and Processed Meat; Dairy Products.; Methods: Index/Score | Follow-up: 5.8 y (median); [underlined: Risk of T2D]:; MDS T2, HR: 0.64, 95% CI: 0.43, 0.49; MDS T3, HR: 0.48, 95% CI: 0.27, 0.83; Summary:; Inverse: MDS & T2D | - Did not account for: Age, Sex, Race/Ethnicity, Physical activity, Smoking, SEP; - Diet assessment: FFQ once (baseline); - Outcomes: Fasted and 2h glucose collected; - Notably large effect size; Significant differences in age, sex, physical activity, smoking across tertiles were not controlled for in analyses; - Funding: NR
Kim & Giovannucci, 2022^79^; Korea; KOGES; Analytic N=7393; Participant characteristics:; - Health: BMI, mean: 24.3–24.8; HTN history: ~10–19%; - Race and/or Ethnicity: NR (Korean); - SEP: Education: ~5–22% ≥ 12y; Selection data: Excluded those with extreme dietary intake; w/ baseline CVD, diabetes, or cancer; refusal/missing info | Age at Dietary Pattern: 40 to 69y; [underlined: Plant-Based Diet Index (PDI) [Satija, 2016]], did not separate fruit juices and veg. oils, Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Tea/coffee; Fruit juices & Veg. Oils; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Negative: Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; [underlined: Healthful PD (hPDI)]: Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Tea/coffee; Negative: Fruit juices & Veg. Oils; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; [underlined: Unhealthful PDI (uPDI):] Negative: Whole grains; Fruits; Vegetables; Nuts; Legumes; Tea/coffee; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; Positive: Fruit juices & Veg. Oils; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Methods: Index/Score | Follow-up: ~15y (S3, 2001 to S8, 2013); [underlined: Risk of T2D]: PDI per 10pt, HR: 0.99, 95% CI: 0.88, 1.12; hPDI per 10pt, HR: 0.86, 95% CI: 0.77, 0.95 (*stronger in those w/ family history T2D, 0.58 (0.44, 0.66) or HTN, 0.73 (0.60, 0.89)); uPDI per 10pt, HR: 1.06, 95% CI: 0.96, 1.18; Summary: Inverse: hPDI & T2D; NS/Positive: uPDI & T2D; NS/Null: PDI & T2D | - Did not account for: Race/Ethnicity (Korean; adjusted for Ansung/Ansan region); - Diet assessment: FFQ at baseline and visit 3 (correlated with 12-d diet); - Outcomes: Fasted (8h+) blood samples collected; T2D based on FBG ≥ 126 mg/dL, Tx with anti-diabetes oral agents or insulin; - Funding: National Research Foundation of Korea (NRF)
Koloverou, 2016 Adherence^80^; Greece; ATTICA; Analytic N=1485; Participant characteristics:; - Health: By Med adherence: Low; Medium; High; - BMI, kg/m2: 29 ± 4.2; 27 ± 2.8; 22 ± 2.5; - WC, cm: 100 ± 12; 92 ± 11;78 ± 10; - Family history of diabetes: 22%; 21%; 22%; - HTN: 46%; 32%; 10%; - Hypercholesterolemic: 44%; 50%; 23%; - Current smoker: 54%; 58%; 51%; - Physically active: 43%; 39%; 44%; - Race and/or Ethnicity: NR (Greek); - SEP: Education, years of school; - Low Med: 11 ± 3.8; - Medium Med: 12 ± 3.6; - High Med: 14 ± 2.8; - Selection data: Included participants who were free of CVD or chronic viral infections, completed the follow-up; Excluded participants with T2D at baseline, with no data on T2D status during follow-up | Age at Dietary Pattern: ~45y [13], mean (enrolled 18 to 89y); [underlined: Mediterranean-based Diet Score(MedDietScore) [Panagiotakos 2007]]: Positive: Vegetables; Potatoes; Legumes; Fruit; Whole Grains; Fish; Olive Oil. Negative: Red and Processed Meat; Poultry; Full-Fat Dairy; Alcohol; Methods: Index/Score | Follow-up: 10 y, T2D; [underlined: Risk of T2D]: T1 (Low), OR: 1, ref; T2 (Medium), OR: 0.51, 95% CI: 0.30, 0.88; T3, (High), OR: 0.38, 95% CI: 0.16, 0.88; Per 1 Unit, OR: 1.04, 95% CI: 0.99, 1.09; Summary: Inverse: MedDietScore & T2D | - Did not account for: Race and/or ethnicity; - Diet assessment: FFQ once; - Outcomes: Fasted (12h+) blood samples collected; T2D based on FBG ≥ 125 mg/dl or use of anti-diabetes meds (ADA criteria); - Stratified analyses, inverse association remained in participants with increased WC: Medium adherence: RR=0.44, 95% CI: 0.25, 0.77; high adherence: RR=0.26, 95% CI: 0.10, 0.70; association was non-significant in participants with normal WC: medium adherence: RR=0.97, 95% CI: 0.29, 3.25; high adherence: RR=0.89, 95% CI: 0.16, 4.90;; - TAC, TNF-α, homocysteine mediated the relationship while oxidized LDL, IL-6, CRP, SAA and fibrinogen did not;; - Other limitations: lack of T2D diagnosis time and thus potential over-estimated effect using OR for HR; possible misclassification of T2D; underreporting and misclassification of diet due to the nature of diet questionnaire assessment; - Funding: NR; Coca-Cola SA for authors DBP & ENG
Koloverou, 2016^(Dietary)81^; Greece; ATTICA; Analytic N=1485; Participant characteristics:; - Health: Among those with T2D at F/U, higher FBG, greater HTN, HC MetSyn, abnormal WHR, and higher initial BMI, WC.; - By those without T2D vs. with T2D at 10y:; - BMI, kg/m2: 26 ± 4.0 vs. 29±5.0; WC, cm: 88 ± 14 vs.98±16; Abnormal WHR ratio: 34% vs. 59%; - HTN: 27% vs.46%; - HC: 37% vs.56%; - Family history of diabetes: 20% vs. 36%; - FBG, mg/dl: 88 ± 12 vs. 95 ± 14; - MetSyn: 12% vs. 30%; - Physically active: 43% vs. 38%; - Current smokers: 54% vs.52%; - Race and/or Ethnicity: NR (Greek); - SEP: Education years of school; - Participants without diabetes: 13 ± 3.4; Participants with diabetes: 14 ± 3.4 Selection data: Included participants who were free of CVD and chronic viral infections at baseline, completed 2011–2012 F/U. Excluded participants who had diabetes at baseline, and those for whom information about diabetes status | Age at Dietary Pattern: ~45y [13], mean (enrolled 18 to 89y); [underlined: Factor 1]: Positive: Red or white meat (beef, pork, and poultry) and potatoes (fried, boiled, or baked); [underlined: Factor 2]: Positive: Fruits, vegetables, legumes, bread, pasta, rusk; [underlined: Factor 3]: Positive: Processed meat, feta cheese, hard cheese; [underlined: Factor 4]: Positive: Fish; [underlined: Factor 5]: Positive: Nuts and sweets; [underlined: Factor 6:] Positive: Dairy (milk, yogurt) and cereals; Methods: Factor or cluster analysis | Follow-up: 10 y, T2D; [underlined: Risk of T2D]: Age group <45 y; Factor 1, OR: 0.99, 95% CI: 0.49, 2.03; Factor 2, OR: 1.89, 95% CI: 0.85, 4.18; Factor 3, OR: 0.86, 95% CI: 0.39, 1.88; Factor 4, OR: 1.12, 95% CI: 0.44, 2.84; Factor 5, OR: 1.19, 95% CI: 0.58, 2.53; Factor 6, OR: 1.23, 95% CI: 0.60, 2.50; Age group: 45–55 years; Factor 1, OR: 0.79, 95% CI: 0.39, 1.59; Factor 2, OR: 0.60, 95% CI: 0.34, 1.07; Factor 3, OR: 0.80, 95% CI: 0.38, 1.69; Factor 4, OR: 1.43, 95% CI: 0.75, 2.72; Factor 5, OR: 1.37, 95% CI: 0.84, 2.25; Factor 6, OR: 1.12, 95% CI: 0.62, 2.03; Age group: > 55 years; Factor 1, OR: 0.93, 95% CI: 0.11, 7.47; Factor 2, OR: 0.19, 95% CI: 0.02, 2.03; Factor 3, OR: 0.18, 95% CI: 0.004, 7.6; Factor 4, OR: 10.6, 95% CI: 0.062, 18.34; Factor 5, OR: 1.40, 95% CI: 0.32, 6.18; Factor 6, OR: 22.3, 95% CI: 0.25, 20.2; Summary: Inverse, NS: Higher; Factor 2 & Lower T2D in age group 45–55 y; Null: Factor 1~6 & T2D in all age group (except 2 in 45–55 y) | - Did not account for: Age (analysed by age group), Race and/or ethnicity, Physical Activity, Alcohol, SEP, Other: TEI (only in sensitivity analysis); - Diet assessment: FFQ once; - Outcomes: Evaluation of medical record; - Adjusting for the percentage of calories from carbohydrates for Factor 2 in 45–55 y group: OR 0.62, 95% CI: 0.34, 1.13; adjusting for total energy intake: OR 0.72, 95% CI: 0.35, 1.49; - Other limitations: unknown time to onset of T2D, underestimation or misclassification of T2D; reduced power from stratification analyses; medium lost-to followup rate (15%); residual confounding; - Funding: Hellenic Cardiology Society; the Hellenic Atherosclerosis Society; Authors DBP & ENG received funding from Coca-Cola SA
Kroger et al and Interact Consortium, 2014^82^; Europe: Denmark, France, Germany, Italy, the Netherlands, Spain, Sweden; UK; EPIC-InterAct; Analytic N=21,616 total; Cases: 9,682; Subcohort: 12,595; Participant characteristics:; - Health: In subcohort:; - BMI, kg/m2: 25.7; - WC, cm, men: 95.0; ♀: 80.0; - Physically active: 21.1%; - Never smoking: 46.2%; - Alcohol, g/d: 7.1; - Race and/or Ethnicity: NR; France: 4%; Spain: 28%; UK-Norfolk: 7%; UK-Oxford: 2%; Netherlands: 11%; Germany: 16%; Sweden: 15%; Denmark: 17%; - SEP: Post-secondary education: 22%; Selection data: EPIC-InterAct included participants without stored blood or without information on reported diabetes. Excluded individuals with prevalent diabetes or uncertain diabetes status; from study centers in Italy and Umea; data from UK centre for DASH only; and those with missing data on diet or covariates. | Age at Dietary Pattern: 25 to 79 y; [underlined: Alternative Healthy Eating Index(AHEI) [McCullough 2002]]: Positive: Vegetables (not potatoes, French fries); Fruit; Nuts and Soy Protein; Cereal Fiber; White: Red Meat Ratio; PUFA:SFA; Multi-Vitamin Use. Negative: Trans-UFA. Neutral: Alcohol; [underlined: Dietary Approaches to Stop Hypertension [Sacks 1995], DASH 1995]: Positive: Grains; Vegetables; Nuts/seeds/legumes; Fruits; Dairy products; Negative: Meat/Poultry/Fish; Fats and oils; Sweets; [underlined: RRR1, inflammatory markers]: Positive: Cabbages; Vegetables, root; Coffee; Wine. Negative: Processed meat; Refined grains; Sugar-sweetened soft drinks; Diet soft drinks; [underlined: RRR2, diabetes-related biomarkers]: Positive: Fruits; Negative: Red meat, beer, poultry, legumes, sugar-sweetened soft drinks, processed meat and white bread; [underlined: RRR3, HOMA-IR index]: Positive: breakfast cereals, honey/jam/sugar, dressing sauces, non-white bread; Negative: diet soft drinks, sugar-sweetened soft drinks, processed meat, salty biscuits and white bread; Methods: Index/Score and RRR | Follow-up: 16y total (median/mean NR); [underlined: Risk of T2D]: Q1, HR: 1, ref; aHEI; Q2, HR: 0.92, 95% CI: 0.82, 1.02; Q3, HR: 0.95, 95% CI: 0.86, 1.06; Q4, HR: 0.95, 95% CI: 0.85, 1.05; Q5, HR: 0.96, 95% CI: 0.86, 1.07; P-trend=0.65; DASH; Q2, HR: 0.96, 95% CI: 0.86, 1.07; Q3, HR: 0.94, 95% CI: 0.84, 1.05; Q4, HR: 0.93, 95% CI: 0.83, 1.04; Q5, HR: 0.95, 95% CI: 0.84, 1.07; P-trend=0.24; RRR1; Q2, HR: 0.92, 95% CI: 0.83, 1.02; Q3, HR: 0.91, 95% CI: 0.82, 1.02; Q4, HR: 0.81, 95% CI: 0.72, 0.91; Q5, HR: 0.76, 95% CI: 0.67, 0.86; P for trend<0.0001; RRR2; Q2, HR: 0.98, 95% CI: 0.89, 1.09; Q3, HR: 0.95, 95% CI: 0.85, 1.06; Q4, HR: 0.90, 95% CI: 0.79, 1.01; Q5, HR: 0.85, 95% CI: 0.75, 0.97; P for trend=0.02; RRR3; Q1, HR: 1, ref; Q2, HR: 0.84, 95% CI: 0.76, 0.93; Q3, HR: 0.84, 95% CI: 0.76, 0.94; Q4, HR: 0.82, 95% CI: 0.73, 0.91; Q5, HR: 0.65, 95% CI: 0.58, 0.73; P for trend<0.0001; Summary: Null: aHEI, DASH & T2D; Inverse: Higher RRR1, RRR2, RRR3 & Lower T2D | - Did not account for: Race and/or ethnicity; Alcohol (DASH, RRR3); Family history of diabetes; - Diet assessment: FFQ once; - Outcomes: Combination of self-report, linkage to primaryor secondary-care registers, medication use (drug registers), hospital admissions and mortality data; - Excluding participants with baseline HbA1c ≥ 6.5%, incident diabetes in the first 2y of F/U, or with CVD, or with extreme TEI (top/bottom 1%); or adjusting for history of diabetes in a first-degree relative did not material change the effect estimates.; - Funding: EU FP6 program; Dutch research council; NL Agency grant; the Board of the UMC Utrecht; Health Research Fund (FIS) of the Spanish Ministry of Health, Navarre Regional Government and CIBER Epidemiología y Salud Pública; Spanish Ministry of Health
Lacoppidan, 2015^83^; Denmark; Danish Diet, Cancer and Health Cohort Study; Analytic N=55,060; Participant characteristics:; - Health:; - BMI, kg/m2: ♀ 24.8, ♂26.1; - WC, cm: ♀ 80, ♂ 89; - Smoking,; - Never: ♀44% ,♂ 26%;; - Former: ♀23% ,♂ 35%;; - Current: 33%, ♂ 40%; - Alcohol ≤12 g/d: ♀3%, ♂ 2%; >12g/d: ♀39%, ♂42%; - Participate in sports: ♀ 59%, ♂ 49%; - Race and/or Ethnicity: NR (Danish); - SEP: Education,; - Women: ≤7 y: 31% 8–10 y: 50% ≥ 11 y: 19%; - ♂ ≤7 y: 35%; 8–10 y: 42%; ≥ 11 y 24%; Selection data: Excluded participants with cancer and/or T2D before baseline, missing information on the exposure or potential confounders, deceased | Age at Dietary Pattern: 56y, mean (50 to 64 y); [underlined: Healthy Nordic Food Index (HNFI) [Olsen 2011],] Positive: Cabbage; Root Vegetables; Apples and Pears; Rye Bread; Oatmeal; Fish; Methods: Index/Score | Follow-up: 15.3 y median, T2D; [underlined: Risk of T2D]: 0, HR: 1, ref; ♀ Per 1-pt, HR: 0.97, 95% CI: 0.94, 1.00; ♀ 1, HR: 1.01, 95% CI: 0.83, 1.23; ♀ 2, HR: 1.02, 95% CI: 0.85, 1.24; ♀ 3, HR: 0.97, 95% CI: 0.80, 1.18; ♀ 4, HR: 0.96, 95% CI: 0.79, 1.17; ♀ 5–6, HR: 0.89, 95% CI: 0.72, 1.10; ♀ p-trend=0.0436; ♂ Per 1-pt, HR: 0.95, 95% CI: 0.93, 0.98; ♂ 1, HR: 0.96, 95% CI: 0.85, 1.09; ♂ 2, HR: 0.98, 95% CI: 0.86, 1.11; ♂ 3, HR: 0.89, 95% CI: 0.78, 1.02; ♂ 4, HR: 0.83, 95% CI: 0.72, 0.95; ♂ 5–6, HR: 0.80, 95% CI: 0.69, 0.94; ♂ p-trend < 0.0001; Summary: Inverse: HNFI & T2D | - Did not account for: Race and/or ethnicity, Family history of diabetes; - Diet assessment: FFQ once; - Outcomes: T2D based on national registries, may include T1D; - Sensitivity analysis by including only confirmed cases yielded slightly stronger inverse association; no interaction between index and BMI.; - Other: measurement error; potential confounding from rapeseed oil, and residual confounding; - Funding: NordForsk and the Danish Cancer Society
Langmann, 2023 ^84^; Denmark; Danish Diet, Cancer and Health Cohort Study; Analytic N=54232; Participant characteristics:; - Health: mean BMI 26 [4]; mean WC 81.9 cm(♀); 95.9 (men); - Race and/or Ethnicity: NR (Danish); - SEP: Education: Long 22%, Medium 40%, Short 23%, Vocational 15%; Selection data: Excluded those with previous diabetes or cancer | Age at Dietary Pattern: 56y, median (50 to 64y); [underlined: EAT-Lancet Reference Diet [Vallejo, 2022; EAT-Lancet Commission, 2019]] Positive: Whole grains & fiber; Vegetables, ≥ 200 - ≤ 600 g/d; Fruits, ≥ 100 - ≤ 300 g/d; All nuts, ≥ 25 g/d. Negative: Dairy foods, ≤ 500 g/d; Beef and lamb, ≤ 14 g/d; Pork, ≤ 14 g/d; Chicken and other poultry, ≤ 58 g/d; Eggs, ≤ 25 g/d; Fish, ≤ 100 g/d; Dry beans, lentils & peas, ≤ 100 g/d; Soy foods, ≤ 50 g/d; Palm oil, ≤ 6.8 g/d; Lard or tallow, ≤ 5 g/d; Butter, 0 g/d; All sweeteners, ≤ 31 g/d. Neutral: Tubers or starchy vegetables, ≤ 100 g/d; Unsaturated oils, ≥ 20 - ≤ 80 g/d; [underlined: Alternative HEI-2010 [Chiuve 2012]AHEI-2010], Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol; Methods: Index/Score | Follow-up: 15y median; [underlined: Risk of T2D]: EAT-Lancet & T2D; perSD, HR: 0.94, 95% CI: 0.91, 0.96; 0–7, HR: 1, ref; 8, HR: 0.91, 95% CI: 0.84, 0.98; 9, HR: 0.89, 95% CI: 0.83, 0.97; 10, HR: 0.83, 95% CI: 0.76, 0.90; 11–14, HR: 0.81, 95% CI: 0.73, 0.89 AHEI-2010 & T2D; per SD, HR: 0.90, 95% CI: 0.87, 0.93; 13–40, HR: 1, ref; 13–40, HR: 0.96, 95% CI: 0.89, 1.03; 41–46, HR: 0.87, 95% CI: 0.81, 0.94; 47–52, HR: 0.86, 95% CI: 0.79, 0.93; 59–110, HR: 0.75, 95% CI: 0.68, 0.82; Summary: Inverse: EAT-Lancet & T2D; Inverse: AHEI-2010 & T2D | - Did not account for: Family history of diabetes, Race/Ethnicity (all Danish); - Diet assessment: FFQ once; - Outcomes: T2D based on registry linkage (e.g., 5 FPG total or 2FPG/5y; med purchases), may include T1D; - 7130 cases; - Funding: Aarhus University; Danish Cancer Society
Laouali, 2021^85^; France; E3N study; Analytic N=70,991; Participant characteristics:; - Health: T2D subcohort:; - BMI, kg/m2: 22.89 ± 3.2; - BMI, > 25 kg/m2: 19.5%; - T2D: 4.6%; HC: 7.1%; HTN: 51.5%; - Smoking: Current: 13.5%, Former: 32.8%, Never: 53.7%; - PA, MET-h/wk: 49.4±50.5; - Family history of diabetes: 11.1%; - Race and/or Ethnicity: NR (French); - SEP: Education in T2D subsample; - Undergraduate or less: 11.09%; - Graduate: 53.12%; - Postgraduate or more: 35.79%; Selection data: Eligible were participants completed a baseline dietary questionnaire in 1993. Excluded prevalent cases of T2D or HTN for each analysis; ♀ with extreme TEI; ♀ who did not complete any follow-up questionnaire after the dietary questionnaire | Age at Dietary Pattern: 53 [7] y; [underlined: Plant-Based Diet Index (PDI) [Satija, 2016],] Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Negative: Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; [underlined: Healthful PDI (hPDI)]: Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Negative: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; [underlined: Unhealthful PDI (uPDI):] Negative: Whole grains; Fruits; Vegetables; Nuts; Legumes; Vegetable oils; Tea/coffee; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; Positive: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Methods: Index/Score | Follow-up: ~20 y f/u, T2D, HTN; [underlined: Risk of T2D]: PDI; Q1, HR: 1, ref; Q2, HR: 0.88, 95% CI: 0.80, 0.97; Q3, HR: 0.82, 95% CI: 0.74, 0.91; Q4, HR: 0.72, 95% CI: 0.64, 0.80; Q5, HR: 0.71, 95% CI: 0.63, 0.79; P-trend<0.0001; Per 1-SD, HR: 0.88, 95% CI: 0.85, 0.91; hPDI; Q1, HR: 1, ref; Q2, HR: 0.99, 95% CI: 0.89, 1.10; Q3, HR: 0.85, 95% CI: 0.77, 0.94; Q4, HR: 0.82, 95% CI: 0.73, 0.92; Q5, HR: 0.74, 95% CI: 0.67, 0.83; P-trend<0.0001; Per 1-SD, HR: 0.88, 95% CI: 0.85, 0.92; uPDI; Q1, HR: 1, ref; Q2, HR: 1.05, 95% CI: 0.95, 1.16; Q3, HR: 0.94, 95% CI: 0.84, 1.05; Q4, HR: 0.91, 95% CI: 0.81, 1.02; Q5, HR: 0.99, 95% CI: 0.89, 1.11; P-trend=0.1904; Per 1-SD, HR: 0.98, 95% CI: 0.94, 1.01; Summary: Inverse: PDI, hPDI & T2D; Null: uPDI & T2D | - Did not account for: Race and/or ethnicity, Alcohol; - Diet assessment: FFQ once in 1993; - Outcomes: Self-report confirmed with reported F/U. Incident T2D cases defined before 2004 as: FPG ≥ 7 mmol/L or NFG ≥ 11.1 mmol/L at diagnosis; or recent HbA1C ≥ 7% (53 mmol/mol); or on anti-diabetes agents; After 2004: cases based on drug reimbursement database (reimbursed 2x/y); - Limited generalizability of population; potential misclassification of T2D and HTN due to change of assessment method would lead to underestimated indicidence; - Funding: IDEX Paris Saclay, the Nutriperso Project; the Mutuelle Générale de l’Education Nationale, the Institut GUSTAVE ROUSSY and the Ligue contre le Cancer; the National Research Agency. “Investissement d’avenir” program “Investissement d’avenir”, “Ministère de
Lee, 2019^(Diabetes-related)^ ^86^; Korea; KOGES; Analytic N=7255; men: 3425; ♀: 3830; Participant characteristics:; - Health: BMI, kg/m2: 24.4 ± 3.1; - Current Smoker: 25.1%; - HTN: 14.2%; - FPG, mg/dL: 82.0 (77.0–88.0); - HbA1c, %: 5.5 (5.3–5.8); - HOMA-IR: 1.4 (1.0–1.9); - Parental history of diabetes: 7.7%; - Dyslipidemia: 2.6%; - Alcohol intake, none: 52.5% .25 g/d: 12.0%; - PA, MET-h/wk: 135.6 (80.5 −245.9); - Race and/or Ethnicity: NR (Korean); - SEP: Education level,; - Did not graduate HS: 54.5%; - Graduated HS: 31.7%; - Some college or higher: 13.8%; - Rural region: 48.6%; Selection data: Included participants who had participated in ≥1 F/U survey. Excluded individuals who had missing baseline dietary survey data, extreme TEI, history of MI, stroke, CVD, or diabetes at baseline, missing data for FBG, HbA1c, or HOMA-IR; or high FBG (≥126 mg/dL) and HbA1c (≥6.5%) at baseline. | Age at Dietary Pattern: 51.5y, mean (40 to 69 y baseline); Men: Positive: Soybeans, nuts and seeds, kimchi, beef, other mean, fish, coffee; Negative: noodles, processed meat, carbonated drinks; wo♂: Positive: Rice, Kimchi, Fruit Negative: Bread, sugar, mushrooms, pork, fish, shellfish; Methods: RRR | Follow-up: 11.5 y (7.8–11.8 y) median (IQR), T2D; [underlined: Risk of T2D]: Men; Q1, HR: 1, ref; Q2, HR: 0.92, 95% CI: 0.68, 1.23; Q3, HR: 0.88, 95% CI: 0.66, 1.19; Q4, HR: 1.27, 95% CI: 0.97, 1.67; Women; Q1, HR: 1, ref; Q2, HR: 0.87, 95% CI: 0.64, 1.18; Q3, HR: 1.02, 95% CI: 0.75, 1.38; Q4, HR: 1.15, 95% CI: 0.83, 1.57; Summary: Null: Either dietary pattern in ♂ or ♀ & T2D | - Did not account for: Race and/or ethnicity (Korean men and ♀); - Diet assessment: FFQ once; - Outcomes: Fasted (12h+) blood samples (FPG; Insulin) collected; T2D via FBG ≥ 126 mg/dl, HbA1C ≥ 6.5%, or self-report physician diagnosis; HOMA-IR=PG x FI/22.5; - Risks before adjust BMI, ♂: Q1: HR 1; Q2: 0.90, 95% CI: 0.67, 1.22; Q3: 0.91, 95% CI: 0.67, 1.22; Q4: 1.38, 95% CI: 1.05, 1.82; in ♀: Q1: HR 1, Q2: HR 0.90, 95% CI: 0.66, 1.21; Q3: 1.04, 95% CI: 0.77, 1.41; Q4: 1.20, 95% CI:0.87, 1.65. No interaction between BMI and DP. HRs ♂ with BMI<23.0, Q1: HR 1; Q2: 0.80, 95% CI: 0.44, 1.44; Q3: 0.76, 95% CI: 0.41, 1.41; Q4: 1.17, 95% CI: 0.66, 2.06; with BMI 23~25.0: Q1: HR 1; Q2: 0.77, 95% CI: 0.43, 1.38; Q3: 0.60, 95% CI: 0.33, 1.08; Q4: 0.88, 95% CI: 0.51, 1.50; with BMI ≥25.0: Q1: HR 1, Q2: 1.09, 95% CI: 0.70, 1.70; Q3: 1.21, 95% CI: 0.78, 1.87;l Q4: 1.72, 95% CI: 1.15, 2.56. In men with history of HTN: Q4 v. Q1: HR 0.99, 95% CI: 0.51, 1.92; without histroy of HTN: Q4 v. Q1: HR 1.32, 95% CI: 0.97, 1.79; with history of dyslipidemia:0.19, 95%CI: 0.06, 0.65; without history of dyslipidemia: 1.42, 95% CI: 1.07, 1.88; in ♀ with history of HTN: Q4 v. Q1: 0.68, 95% CI: 0.38, 1.23; without history of HTN: 1.37, 95% CI: 0.94, 2.00; in ♀ with history of dyslipidemia: 0.30, 95% CI: 0.03, 2.62; without history of HTN: 1.17, 95% CI: 0.85, 1.62; - Limited generalizability of population; Culturally-specific food groups; - Funding: Basic Science Research Program through the National Research Foundation of Korea (NRF) funded by the Ministry of Education
Lee, 2019^(Identification)87^; Korea; KOGES; Analytic N=55457; men: 18,292; ♀: 37165; Participant characteristics:; - Health: Range from ‘Prudent’ quantiles ♂; ♀; - BMI, kg/m2: 24.2–24.5; 23.3–23.6; - Current smokers: 26–28%; 1.5–2%; - Alcohol, g/d: 13.9 to 18.7; 1.6 to 1.8; - Regular PA 54–66%; 45–62%; - Family history of diabetes: 13–15%; 18–19%; - Race and/or Ethnicity: NR (Korean); - SEP: Education, college or higher, %, by “Prudent” pattern, quantiles:; - In men: 43.9%; 45.2%; 47.6%; - In ♀: 24.3%; 24.5%; 27.2%; Selection data: Eligible were participants who completed the follow-up survey between 2012 and 2016. Excluded participants with T2D or Cancer at baseline, who had no dietary data, implausible dietary intake, and/or missing covariate data | Age at Dietary Pattern: 40 to 69 y; [underlined: “Prudent”:] Positive: vegetables (lightcolored, green/yellow), lean fish, seaweeds, mushrooms, shellfish, kimchi, bone fish, pickled vegetables, fruits, tubers, legumes and soy products, milk, salt-fermented fish (men only), yogurt and fatty fish( ♀ only); [underlined: “Fatty fish, meat, and flour-based food]“: Positive: fatty fish, pizza/hamburger, processed meats, high-fat red meat, bread, poultry, red meat by-products, cake/snack/cookie, noodles/dumpling, dairy products (men only), other seafood, carbonated beverages, red meat; [underlined: “Coffee and Sweets”:] Positive: Sweets, Oils/fats, Coffee; [underlined: “White Rice”:] whole grain (positive for men, negative for ♀), white rice (positive for ♀, negative for men); Methods: Factor or cluster analysis | Follow-up: 4.9 y mean, T2D; [underlined: Risk of T2D]: Incident; T2D/hyperglycemia; “Prudent” in Men; Q1, HR: 1, ref; Q3, HR: 1.07, 95% CI: 0.89, 1.29; Q5, HR: 0.93, 95% CI: 0.75, 1.15; P-trend=0.4457; “Prudent” in Women; Q1, HR: 1, ref; Q3, HR: 0.91, 95% CI: 0.77, 0.99; Q5, HR: 0.75, 95% CI: 0.63, 0.89; P-trend=0.0003; “Fatty fish, meat, and flour-based food” in Men; Q1, HR: 1, ref; Q3, HR: 1.10, 95% CI: 0.91, 1.32; Q5, HR: 1.04, 95% CI: 0.83, 1.30; P for trend=0.6834; in Women; Q1, HR: 1, ref; Q3, HR: 1.13, 95% CI: 0.92, 1.38; Q5, HR: 1.22, 95% CI: 1.03, 1.44; P for trend=0.0210; “Coffee and sweets” pattern ♂; Q1, HR: 1, ref; Q3, HR: 1.20, 95% CI: 0.99, 1.45; Q5, HR: 1.06, 95% CI: 0.87, 1.30; P for trend=0.7622; in ♀; Q1, HR: 1, ref; Q3, HR: 0.97, 95% CI: 0.82, 1.15; Q5, HR: 0.94, 95% CI: 0.80, 1.11; P for trend=0.7350; “Whole grain/white rice” ♂; Q1, HR: 1, ref; Q3, HR: 0.99, 95% CI: 0.82, 1.19; Q5, HR: 0.98, 95% CI: 0.80, 1.21; P for trend=0.9672; in ♀; Q1, HR: 1, ref; Q3, HR: 1.01, 95% CI: 0.84, 1.20; Q5, HR: 0.99, 95% CI: 0.82, 1.19; P for trend=0.4459; Summary: Inverse: “Prudent” & T2D in ♀; Positive: “fatty fish, meat, and flour-based food” & T2D in ♀; Null: “Prudent” “fatty fish, meat and flour-based food” & T2D ♂; “coffee and sweets”, “white rice” & T2D ♂ and ♀ | - Did not account for: Race and/or ethnicity (Korean men and ♀); - Diet assessment: FFQ once, validated with 3d records; - Outcomes: Self-report of physician diagnosis or FBG ≥ 126 mg/dl; - Funding: n/a
Lee, 2020^88^; USA; HPFS/NHS I, NHS II; Analytic N=204,995; Participant characteristics:; - Health: BMI ~ 23–26 by EDIP/H quntiles (Q5 higher v. Q1); - Race and/or Ethnicity: 95–99% White; - SEP: NR, all health professionals; Selection data: Excluded those with diabetes, CVD, or Cancer (except nonmelanoma skin cancer) at baseline; those with incomplete or implausible dietary data; | Age at Dietary Pattern: ~42y (NHS, II), ~56y (NHS/HPFS), means at dietary pattern (25 to 75 y at enrollment); [underlined: Empirical dietary inflammatory pattern (EDIP)] [Tabung, 2016][underlined: ,] Anti-inflammatory group: tea, coffee, dark yellow vegetables (carrots, or squash), leafy green vegetables (cabbage, spinach, or lettuce), snacks (cracker, or potato chips), fruit juice (apple juice, cantaloupe juice, orange juice, or other fruit juice), pizza. Pro-inflammatory group: processed meat (sausage), red meat (beef, or lamb), organ meat (beef, calf, or chicken liver), other fish (canned tuna, or fish), other vegetables (mixed vegetables, green pepper, cooked mushroom, eggplant, zucchini, or cucumber), refined grains (white bread, biscuit, white rice, pasta, or vermicelli), high-energy and low energy beverages (cola with sugar, carbonated beverages with sugar, fruit punch drinks), and tomatoes; [underlined: Empirical dietary index for hyperinsulinemia (EDIH)] [Tabung, 2016], Positive: Red meat; Processed meat; Poultry; Tomatoes; French fries, Fish (other than dark-meat fish); Low-fat dairy; Eggs; High-energy beverages (cola and other carbonated beverages with sugar, fruit drinks); Low-energy beverages; Margarine; Cream soups; Negative: Green leafy vegetables; Whole fruit; High-fat dairy products; Coffee; Wine; Methods: Index/Score | Follow-up: 32y total (median/mean NR); [underlined: Risk of T2D]: Incident T2D - EDIP (pooled); Q1, HR: 1, ref; Q2, HR: 1.28, 95% CI: 1.20, 1.35; Q3, HR: 1.41, 95% CI: 1.33, 1.49; Q4, HR: 1.65, 95% CI: 1.57, 1.74; Q5, HR: 1.95, 95% CI: 1.85, 2.05; p-trend<0.001; Incident T2D - EDIH (pooled); Q1, HR: 1, ref; Q2, HR: 1.19, 95% CI: 1.12, 1.26; Q3, HR: 1.37, 95% CI: 1.30, 1.45; Q4, HR: 1.54, 95% CI: 1.46, 1.63; Q5, HR: 1.87, 95% CI: 1.78, 1.98; p-trend<0.001; Summary: Positive: EDIH & T2D, ♀ + ♂ (♀; ♂); Positive: EDIP & T2D, ♀ + ♂ (♀; ♂) | - Did not account for: Sex (pooled analyses); - SEP (all health professionals); - Diet assessment: FFQ every 4y, validated; - Outcomes: Self-report confirmed with reported f/u based on NDDG criteria: classic symptoms and FPG ≥ 7.8 mmol/L (140 mg/dL; post-2010, 7 mmol/L) or NF ≥ 11.1 mmol/L (200 mg/dL); or no symptoms but 2+ elevated FBG or nonfasted on different occasions or after OGTT; or on anti-diabetic agents; or HbA1C ≥ 6.5% post-2010;; - Identified 19.7K cases; Results similar when cohorts/sexstratified (NHS, NHS II, HPFS). Subgroup analyses revealed stronger positive association between EDIP & T2D among younger, leaner, or more active adults or those w/out family history of diabetes. Stronger positive association between; - EDIH & T2D among younger, leaner, or more active adults, never smokers, or moderate drinkers; - Funding: NIH, Boston Nutrition Obesity Research Center
Ley, 2016 ^89^; USA; HPFS/NHS I, NHS II; Analytic N=124,607; NHS: 48,612; NHS II: 49,711; HPFS: 26,284; Participant characteristics:; - Health: By NHS-I; NHS II; HPFS; - BMI, kg/m2: 24.9–25.1; 24.6–25.4; 25.2–25.3; - PA, MET-h/wk: 13.8–16.0; 19.2–24.0; 21–24; - Current smoker: ~16%; 11–12%; 7–9%; - HTN: 22–24%; 10–13%; 15–16%; - HC: 31–38%; 23–25%; 16–28%; - Family history of diabetes: ~28%; ~37%; ~21%; - Race and/or Ethnicity: 95–99% White; - SEP: NR, all health professionals; Selection data: Excluded participants with or with history of CVD or Cancer, who died during 1^st^ 4y F/U; missing data (FFQ, >10 FFQ items, date of birth, BMI or physical activity at baseline), pregnant during FFQ cycle, or who reported implausible TEI. | Age at Dietary Pattern: ~42y (NHS, II), ~56y (NHS/HPFS), mean at dietary pattern (25 to 75 y at enrollment); Dietary pattern: Alternative HEI (AHEI)-2010 [Chiuve 2012]: Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol; Methods: Index/Score | Follow-up: ~ 16 y for NHS II; ~ 20 y for NHS and HPFS; [underlined: Risk of T2D]: NHS; Mod-Lg. ↓, HR: 1.27, 95% CI: 1.13, 1.43; Sm.-Mod.↓ HR: 1.04, 95% CI: 0.95, 1.13; Stable, HR: 1, ref; Sm.-Mod ↑, HR: 0.95, 95% CI: 0.88, 1.03; Mod-Lg. ↑, HR: 0.89, 95% CI: 0.80, 0.99; P-trend<0.0001; per 10% ↑, HR: 0.89, 95% CI: 0.85, 0.93; NHS II; Mod-Lg. ↓,, HR: 1.31, 95% CI: 1.13, 1.51; Sm.-Mod.↓ , HR: 1.03, 95% CI: 0.93, 1.15; Stable, HR: 1, ref; Sm.-Mod ↑, HR: 0.88, 95% CI: 0.80, 0.98; Mod-Lg. ↑, HR: 0.77, 95% CI: 0.69, 0.87; P-trend<0.0001; Per 10%, HR: 0.85, 95% CI: 0.81, 0.89; HPFS; Mod-Lg. ↓,, HR: 1.05, 95% CI: 0.86, 1.30; Sm.-Mod.↓ , HR: 0.98, 95% CI: 0.86, 1.13; Stable, HR: 1, ref; Sm.-Mod ↑, HR: 0.94, 95% CI: 0.83, 1.07; Mod-Lg. ↑, HR: 1.01, 95% CI: 0.86, 1.18; p-trend=0.67; Per 10%, HR: 0.97, 95% CI: 0.91, 1.04; Pooled; Mod-Lg. ↓, HR: 1.25, 95% CI: 1.15, 1.36; Sm.-Mod ↑, HR: 1.03, 95% CI: 0.97, 1.09; Stable, HR: 1, ref; Sm.-Mod ↑, HR: 0.93, 95% CI: 0.88, 0.98; Mod-Lg. ↑ HR: 0.86, 95% CI: 0.81, 0.93; p-trend<000.0001; Per 10%, HR: 0.89, 95% CI: 0.86, 0.91; Summary: Direct: Moderate to Large (>10%) decrease in AHEI & higher T2D in ♀ (NHS or NHS II) and ♀ + ♂; Small or Moderate to Large (>10%) increase in AHEI & lower T2D in ♀ (NHS or NHS II) and ♀ + ♂; NS/Direct: AHEI & T2D in only HPFS | - Did not account for: Sex (pooled analysis), SEP (though all health professionals); - Diet assessment: FFQ every 4y, change assessed; - Outcomes: Self-report confirmed based on classic symptoms and FPG ≥ 7.8 mmol/L (7 mmol/L post-1998) or NF ≥ 11.1 mmol/L; or no symptoms but 2+ elevated FBG or non-fasted on different occasions or after OGTT; or on anti-diabetic agents; or HbA1C ≥ 6.5% post-2010;; - Identified 9300+ cases; Additional adjustment for changes in body weight resulted in HR 0.91, 95% CI: 0.88,0.93 for per 10% increment; association remained when stratified by baseline diet quality (P interaction=0.2; P for trend≤0.001), baseline BMI (P interaction=0.001, P for trend≤0.01), across physical activity change categories (P interaction=0.8, P for trend≤0.0005), or when AHEI socres were calculated without the long-chain n-3 FA; inverse associations were more pronounced in younger than in older participants; limited generalizibility; - Funding: NIH
Llavero-Valero, 2021 ^90^; Spain; Seguimiento Universidad de Navarra (SUN) cohort; Analytic N=20,060; Participant characteristics:; - Health: mean BMI, T1: 23.2, T2: 23.4, T3: 23.7 (p<0.001); - 14.3–14.5% family history T2D; ~18–21% HTN; 3.2–3.6% cancer; 1.2–1.9% CVD; 10.3–12.9% Depression; Compared to T1 of UPF, those in T3 more likely to be current smokers, have more hypertension, depression, cancer and CVD at baseline; - Race and/or Ethnicity: NR; - SEP: All w/ University degree, > 50% health professionals; - Compared to T1 of UPF, those in T3 more likely to have post-university education; Selection data: Excluded those with: TEI < 1st % or > 99% tile; prevalent T2D at baseline; T1D, other diabetes, pancreatectomy; LFU | Age at Dietary Pattern: 37.4 y, mean; Dietary pattern: Nova Classification, Group 4 “Ultra-processed” (Nova 4) [Monteiro, 2019]: Nova 4: e.g., carbonated soft drinks, sweet or savoury packaged snacks, pastries, cakes and cake mixes, margarine, ‘instant’ sauces, fruit yogurts and fruit drinks, pre-prepared meat, pasta and pizza dishes, or meat and chicken extracts; Methods: Index/Score | Follow-up: 12 y (median); Risk of T2D:; UPF, Nova 4 diet at baseline; T2, HR: 0.99, 95% CI: 0.69, 1.43; T3, HR: 1.53, 95% CI: 1.06, 2.22; p-trend=0.024; UPF, Nova4 diet at 10y F/U; T2, HR: 1.07, 95% CI: 0.74, 1.54; T3, HR: 1.65, 95% CI: 1.14, 2.38; p-trend=0.023; Summary: Positive: UPF & T2D | - Did not account for: Race/Ethnicity (mostly Spanish); - Diet assessment: FFQ at baseline and 10y F/U (change from repeat measures and updated diet accounted for); Misclassification of UPF possible due to FFQ; - Outcomes: Self-report of diagnosis or diabetes-med use; endorcrinologist assessed with F/U report a/o records via ADA criteria; - mean UPF intake ~ 295.8g/d [217.4]; - Funding: Spanish Government-Instituto de Salud Carlos III, European Regional Development Fund, CIBERobn
Lopez, 2022^91^; Mexico; Mexican Teachers Cohort; Analytic N=74671; Participant characteristics:; - Health: 19–21% Ob; 37–39% OW; 32–34% Normal Wt; 13–15% HTN; 69–79% pre-menopause; 12–20% post-menopause; - Race and/or Ethnicity: 100% Mexican, from culturally diverse areas; - SEP: SES: HH assets T1, ~29–33%; T2, 31–34%, T3, 37–44%; Selection data: Included ♀ without diabetes, Stroke, HD, Cancer at baseline; Excluded ♀ with implausible/missing/incomplete dietary intakes or LFU | Age at Dietary Pattern: 41 to 44y, mean (≥25y); Dietary pattern: EAT-Lancet Reference Diet [Vallejo, 2022; EATLacnet Commission, 2019]: EAT-Lancet: Positive: Whole grains & all grains, ≤ 464 g/d and whole grain fiber; Vegetables, ≥ 200 - ≤ 600 g/d; Fruits, ≥ 100 - ≤ 300 g/d; All nuts, ≥ 25 g/d. Negative: Dairy foods, ≤ 500 g/d; Beef and lamb, ≤ 14 g/d; Pork, ≤ 14 g/d; Chicken and other poultry, ≤ 58 g/d; Eggs, ≤ 25 g/d; Fish, ≤ 100 g/d; Dry beans, lentils & peas, ≤ 100 g/d; Soy foods, ≤ 50 g/d; Palm oil, ≤ 6.8 g/d; Lard or tallow, ≤ 5 g/d; Butter, 0 g/d; All sweeteners, ≤ 31 g/d. Neutral: Tubers or starchy vegetables, ≤ 100 g/d; Unsaturated oils, ≥ 20 - ≤ 80 g/d; Methods: Index/Score | Follow-up: ~2y; [underlined: Risk of T2D]: EAT-Lancet & T2D; 0–4, HR: 1.00, ref; 5–6, HR: 0.98, 95% CI: 0.90, 1.08; 7–8, HR: 1.00, 95% CI: 0.90, 1.10; 9–13, HR: 0.90, 95% CI: 0.75, 1.10; Summary: NS/Null: Eat-Lancet & T2D | - Did not account for: Anthropometry; Race/ethncitiy (all Mexican but from culturally diverse areas); - Diet assessment: FFQ once; - Outcomes: Combination of self-report and database linkage used to define T2D; - Identified 3241 cases; - Funding: NR
Ma, 2022^92^; Japan; Fukushima Health Management Survey (FHMS); Analytic N=22740; Participant characteristics:; - Health: 29.8% OW/Ob; mean BMI, 23.4; 39.8% HTN;; - Race and/or Ethnicity: NR (Japanese); - SEP: 26% > vocational; 44% living in temporary shelter; Selection data: Included only evacuees of the Great East Japan Earthquake and Fukushima incident without diabetes at baseline who completed the health checkup and FFQ; Excluded those ≥3 missing FFQs | Age at Dietary Pattern: 55.9y, mean (20 to 89y); typical Japanese’: highest in boiled and fermented beans; fish; fruit; green vegetables, miso soup, red/yellow vegetable, rice, tofu, white vegetable; lowest in bread, fruit juice, vegetable juice; neutral: milk, soy milk,yogurt, beef/pork, chicken, ham/sausage; ‘Juice’: highest in boiled beans, fruit, fruit juice, vegetable juice; soy milk, yogurt (all) and bread and milk ♂ only; lowest in beef/pork; netural: chicken, ham/sausage; ‘Meat’: highest in beef/pork, chicken, ham/sausage (all) and bread (♀ only); Methods: Factor or cluster analysis: PCA | Follow-up: ~7y (2011–2018); [underlined: Risk of T2D]:; ‘typical Japanese’ & T2D; Q2, HR: 0.82, 95% CI: 0.70, 0.96; Q3, HR: 0.83, 95% CI: 0.71, 0.97; Q4, HR: 0.80, 95% CI: 0.68, 0.94; p-trend=0.015 ‘Juice’ DP & T2D; Q2, HR: 1.01, 95% CI: 0.87, 1.17; Q3, HR: 0.90, 95% CI: 0.78, 1.05; Q4, HR: 0.99, 95% CI: 0.86, 1.15; p-trend=0.773 ‘Meat’ DP & T2D; Q2, HR: 1.13, 95% CI: 0.99, 1.29; Q3, HR: 0.91, 95% CI: 0.78, 1.05; Q4, HR: 1.05, 95% CI: 0.90, 1.22; p-trend=0.883; Summary: Inverse: ‘typical Japanese’ & T2D; NS/Null: ‘Juice’ & T2D; NS/Null: ‘Meat’ & T2D | - Did not account for: Family history of diabetes, Race/Ethnicity (Japanese), Other TEI; - Diet assessment: FFQ once; - Outcomes: Fasted (8h+) blood samples collected; T2D based on FBG ≥ 126 mg/dL or selfreported use of anti-diabetic oral agent; - Identified 1.4K cases; Sex-stratified analyses produced similar results; - Funding: National Health Fund for Children and Adults Affected by the Nuclear Incident, Ministry of the Environment, Japan (MOEJ)
Maldonado, 2022^93^; USA; Hispanic Community Health Study/Study of Latinos (HCHS/SOL); Analytic N=7774; Participant characteristics:; - Health: WC ~93–98cm; Majority never smokers (53–81%);; - Race and/or Ethnicity: 100% Hispanic/Latino (majority foreign-born (46–95%): Cuban, Dominican, Mexican, Puerto Rican, Central American, and South American); - SEP: Most > HS education (46–57%); Selection data: Excluded those with diabetes at baseline, no visit 2 data, not fasted for BG, missing/extreme 24-h recall, missing data, reported more than one heritage | Age at Dietary Pattern: 18 to 74y; Description:; - “Burgers, Fries, Soft Drinks”: Positive: Burgers, french fries, fried foods, pizza, sandwiches, soft drinks; - “White Rice, Beans ,& RedMeats”: Positive: Pork, beef, processed meats, white rice; - “Fish & Whole Grain”: Positive: salads, fish, poultry, whole grains; - “Cheese & Sweets”: Positive: cheese, fried foods, desserts, sweets, noodle -based foods, coffee/tea. Negative: white rice; - “Stew & Corn”: Positive: cheese, corn-based foods, meat & vegetable stew, soups. Negative: poultry; Methods: Factor or cluster analysis: PCA | Follow-up: ~6y; [underlined: Risk of T2D]: Q1, OR: 1 ref (95%CI); “Burgers, Fries, Soft drinks”; Cuban; Q2, OR: 0.80(0.43,1.49); Q3, OR: 0.71(0.37,1.38); Q4, OR: 1.00(0.55,1.82); Q5, OR: 0.67(0.33,1.36); Dominican; Q2, OR: 1.36(0.57,3.28); Q3, OR: 1.48(0.61,3.58); Q4, OR: 1.33(0.55,3.24); Q5, OR: 1.53(0.59,3.96); Mexican; Q2, OR: 0.82(0.53,1.28); Q3, OR: 1.20(0.74,1.97); Q4, OR: 1.35(0.86,2.11); Q5, OR: 1.05(0.65,1.69); Puerto Rican; Q2, OR: 1.50(0.83,2.70); Q3, OR: 1.19(0.64,2.22); Q4, OR: 2.30(1.13,4.72); Q5, OR: 2.63(1.29,5.36); CentralAm.; Q2, OR: 1.17(0.53,2.59); Q3, OR: 0.75(0.30,1.90); Q4, OR: 1.03(0.36,2.90); Q5, OR: 1.98(0.66,5.95); S. Am.; Q2, OR: 1.54(0.58,4.09); Q3, OR: 0.95(0.39,2.29); Q4, OR: 0.52(0.16,1.73); Q5, OR: 0.72(0.23,2.23); “White Rice, Beans,& Red Meats” & T2D; Q2, OR: 1.09 (0.57,2.08); Q3, OR: 1.13 (0.50,2.52); Q4, OR: 1.43 (0.73,2.81); Q5, OR: 1.58 (0.80,3.12); Dominican; Q2, OR: 1.76(0.70,4.46); Q3, OR: 1.78(0.59,5.36); Q4, OR: 1.50(0.52,4.31); Q5, OR: 2.16(0.83,5.67); Mexican; Q2, OR: 1.14(0.70,1.86); Q3, OR: 1.31(0.77,2.24); Q4, OR: 1.17(0.74,1.83); Q5, OR: 1.10(0.65,1.88); PuertoRican; Q2, OR: 0.37(0.18,0.78); Q3, OR: 1.20(0.62,2.30); Q4, OR: 0.75(0.37,1.52); Q5, OR: 0.65(0.30,1.39); CentralAm.; Q2, OR: 2.05(0.81,5.19); Q3, OR: 1.72(0.69,4.28); Q4, OR: 2.58(0.96,6.91); Q5, OR: 2.12(0.89,5.02); S. Am. (NR); “Fish & Whole Grains” & T2D; Cuban; Q2, OR: 0.96(0.44, 2.10); Q3, OR: 2.63(1.25, 5.58); Q4, OR: 1.43(0.71, 2.87); Q5, OR: 1.37(0.55, 3.45); Mexican; Q2, OR: 0.84(0.54, 1.32); Q3, OR: 0.89(0.57, 1.38); Q4, OR: 1.28(0.83, 1.99); Q5, OR: 0.89(0.56, 1.42); PuertoRican; Q2, OR: 0.74(0.34, 1.61); Q3, OR: 0.54(0.29, 1.02); Q4, OR: 0.63(0.33, 1.21); Q5, OR: 0.62(0.30, 1.28); S. Am.; Q2, OR: 0.54(0.19, 1.52); Q3, OR: 1.06(0.39, 2.90); Q4, OR: 0.83(0.28, 2.45); Q5, OR: 0.76(0.28, 2.06); “Cheese & Sweets” & T2D; Cuban; Q2, OR: 0.80(0.38, 1.69); Q3, OR: 0.89(0.32, 1.47); Q4, OR: 0.78(0.36, 1.70); Q5, OR: 0.43(0.20, 0.94); S. Am.; Q2, OR: 1.32(0.40, 4.34); Q3, OR: 1.59(0.49, 5.17); Q4, OR: 2.01(0.72 ,5.65); Q5, OR: 1.19(0.36, 3.99); “Stew & Corn” DP & T2D; Puerto Rican; Q2, OR: 1.56(0.72, 3.40); Q3, OR: 0.71(0.34, 1.50); Q4, OR: 0.63(0.29, 1.33); Q5, OR: 0.94(0.47, 1.86); Central Am.; Q2, OR: 1.33(0.46, 3.78); Q3, OR: 1.42(0.63, 3.20); Q4, OR: 1.45(0.61, 3.42); Q5, OR: 1.07(0.38, 2.95); Summary: Inverse (weak): “Cheese & Sweets” (only Q5 v. Q1 in those from Cuba) & T2D; NS/Null otherwise; NS/Null: “Burgers, Fries, Soft Drinks “& T2D; NS/Null:“White Rice, Beans ,& RedMeats” & T2D; NS/Null:“Fish & Whole Grain” & T2D; NS/Null:“Stew & Corn” & T2D | - Did not account for: Smoking, Family history of diabetes; - Diet assessment: 24h recalls, twice; - Outcomes: Fasted (8h+) blood samples collected; T2D based on FBG ≥ 126 mg/dL,OGTT ≥ 20- mg/dL, or HbA1C ≥ 6.5% and self-report of diagnosis or on diabetic-agents,; - 7–17% incidence at 6y; Results have notably wide CIs; Estimates including adjustment for smoking did not change, so smoking was excldued from final models; - Funding: NHLBI; UNC-CH Carolina Population Center; NICHD; NIDDK; University of Miami; Albert Einstein College of Medicine; Northwestern University; San Diego State University
Mandalazi, 2016^94^; Sweden; Malmo Diet and Cancer (MDC) cohort; Analytic N=26,868; Participant characteristics:; - Health: ~ mean BMI, 25–26.2; - From DQIS categories ♂; ♀; - BMI, kg/m2: 25.8 to 26.3; 24.9 to 25.6; - FPG, mmol/L: 5.77 to 5.84; 5.48 to 5.53; - Alcohol use: nonconsumer v. high: 4% v. 21%; 6.1% v. 19.5%; - Smoking status, Current: 15–39%; 18–38%; - Leisure-time PA: 23–35%; 20–30%; - Race and/or Ethnicity: NR (Swedish); - SEP:; - Elementary: 35–53%; - Primary, secondary: 19–31%; - Upper secondary: 7–13%; - Further education, no degree: 8–11%; - University: 11–17%; Selection data: Excluded all with diabetes, T1D cases, Latent Autoimmune Diabetes in Adults, secondary diabetes, or other diabetes-conditions at baseline | Age at Dietary Pattern: 44 to 74 y; Dietary pattern: Diet Quality Index - Swedish Dietary Guidelines (DQI-SNR) [Drake 2011]: Positive: Vegetables and Fruit; Fish and Shellfish. Negative: Sucrose; SFA. Neutral: PUFA; Dietary Fiber; Methods: Index/Score | Follow-up: 17 y mean ( 0–24 y), T2D; [underlined: Risk of T2D]: ♀ + ♂, Medium, HR: 1.03, 95% CI: 0.94, 1.13; ♀ + ♂, High, HR: 1.06, 95% CI: 0.94, 1.20; ♀ + ♂, P-trend=0.56; ♂, Medium, HR: 1.04, 95% CI: 0.91, 1.19; ♂, High, HR: 1.02, 95% CI: 0.84, 1.23; ♂, P-trend=0.96; ♀, Medium, HR: 1.02, 95% CI: 0.90, 1.16; ♀, High, HR: 1.10, 95% CI: 0.93, 1.29; ♀, P-trend=0.40; Summary: NS/Null: DQI-SNR & T2D (♀ + ♂, ♀, or ♂) | - Did not account for: Race and/or ethnicity (Swedish),; - Family history of diabetes; - Diet assessment: Diet history once (validated; interview + 7d menu + Q); - Outcomes: Combination of seven registries (90%) or exams (10%); Diagnosis from FBG ≥ 7 mmol/L and/or 2+ HbA1C ≥ 6%; - 3.8K cases identified; Model without BMI: Medium: HR 1.10, 95% CI: 1.00, 1.20; High: HR 1.17, 95% CI: 1.03, 1.32 (Ptrend=0.02); interaction with sex was not significant (P=0.50); Sensitivity analyses by excluding those who were classified as energy misreporters and those who reported substantial change in food habits in the past resulted an inverse association in basic model but not sig in multivariable model; or including only T2D cases identified by more than one source did not show significantly different results.; - Funding: Swedish Research Council, the Swedish Society for Medical Research, the Crafoord Foundation, the Albert Pahlsson Foundation, Medical Training and Research Agreement
Markanti, 2021^95^; Denmark; Danish Diet, Cancer and Health Cohort Study; Analytic N=54,305; Participant characteristics:; - Health: Median (IQR); - HTN, men: 651 (14.0); 1725 (14.0);1125 (14.9);195 (16.4); - HC, men: 283 (6.1); 916 (7.4); 766 (10.1); 198 (16.6); - HTN, ♀: 349 (16.1); 1742 (16.9); 2093 (16.6); 620 (17.6); - HC, ♀: 104 (4.8); 524 (5.1); 806 (6.4); 318 (9.0); - Race and/or Ethnicity: NR; - SEP: Education (No vocational training; Higher 1–2y; Higher 3–4y; Higher > 4y); - Men, 5–15%; 11–16%; 39–43%; 25–45%,; - Women, 13–35%; 30–32%; 30–41%;6–15%; Selection data: Excluded those with cancer diagnosis at baseline; diabetes at baseline; missing dietary or covariate data; lost to f/u | Age at Dietary Pattern: 50 to 64 y at baseline; Dietary pattern: Danish Dietary Guidelines Index (D-DGI) [Hansen, 2018]: Positive: Fish, Fruits and vegetables, Whole grains; Negative: Red and processed meat; Saturated fat; Sugar; Methods: Index/Score | Follow-up: 15 y (median); [underlined: Risk of T2D]: Incident T2D; ♂, Low-medium, HR: 0.80, 95% CI: 0.74, 0.87; ♂, Medium-high, HR: 0.71, 95% CI: 0.65, 0.78; ♂, High, HR: 0.70, 95% CI: 0.58, 0.85; ♀, Low-medium, HR: 0.98. 95% CI: 0.86, 1.11; ♀, Medium-high, HR: 0.95, 95% CI: 0.83, 1.08; ♀, High, HR: 0.82, 95% CI: 0.69, 0.96; Summary: Inverse: D-DGI & T2D | - Did not account for: Family history of diabetes, Race and/or Ethnicity, Other: TEI; - Diet assessment: FFQ once; - Outcomes: T2D based on national registries, may include T1D; - 7K cases; Notably large effect sizes with narrow Cis; - Funding: NR
Mattei, 2017^96^; USA; Boston Puerto Rican Health Study; Analytic N=1137 for AHEI,; 1140 for AHA-DS,; 1189 for DASH,; 1194 for HEI,; 1194 for MeDS; Participant characteristics:; - Health: AHA-DS Q1; Q5; - Obesity: 51.5%; 57.3%; - Diabetes: 39.9%; 40.3%; - CVD: 16.3%; 23%; - HTN: 64.4%; 67.6%; - Current smoker: 28.1%; 18.4%; - Physical activity score: 31.0 ± 4.5; 32.2 ±4.6; - Psychological acculturation score: 17.5 ±6.4; 20.1 ±7.0; - Eat away from home >1 time/wk: 25.4%; 22.4%; - Race and/or Ethnicity: NR (Puerto Rican); - SEP: AHA-DS Q1; - Ratio of income to poverty: 1.13 ± 0.85; - Education higher than eighth grade: 54.4%; - Married/with partner: 30.0%; - AHA-DS Q5; - Ratio of income to poverty: 1.64 ± 1.8; - Education higher than eighth grade: 64.0%; - Married/with partner: 31.3%; Selection data: Enrolled self-identified Puerto Ricans who responded to home-based interview without severe health conditions or cognitive impairment. Excluded missing/extreme FFQ data | Age at Dietary Pattern: 45 to 75 yr; Dietary pattern: AHA Diet Score (AHA-DS) [Bhupathiraju 2011]; Alternative HEI (AHEI)-2010 [Chiuve 2012]; Healthy Eating Index (HEI-2005) [Guenther 2008]; Mediterranean Diet Score (MDS) [Trichopoulou 2003]; DASH diet modfied [modified Fung, 2008]; - AHA-DS: Positive: Vegetables and Fruit; Variety; Whole Grains; Fish; Negative: SFA; Total fats; Trans Fat; Cholesterol; Added Sugars; Sodium; Neutral: Alcohol; - AHEI-2010: Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol; - HEI-2005: Positive: Total Vegetables; Dark Green/Orange Vegetables, Legumes; Total Fruit; Whole Fruit; Whole Grains; Total Grains; Meat and Beans; Milk, Yogurt, Cheese, and Soy Beverages; Healthy Oils. Negative: SFA; Solid fats, Alcohol, and Added Sugars; Sodium; - MDS: Positive: Vegetables; Legumes (and beans); Fruit (and Orange juice), Nuts; Whole grains (oatmeal); Fish (traditional); MUFA/SFA (corn oil). Negative: Red and Processed Meat; Dairy Products (Whole Milk). Neutral: Alcohol (Beer); - DASH: Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Total dairy; Negative: Red and Processed Meat; Sweetened beverages; Sodium; Methods: Index/Score | Follow-up: 2 y, Biomarkers; [underlined: HbA1C:] %; AHA-DS: −0.06 (0.04); DASH: −0.02 (0.04); HEI: −0.06 (0.04); MeDS:-0.05 (0.04); AHEI: −0.04 (0.04); [underlined: Glucose:] loq-serum qlucose, mq/dl; AHA-DS:-0.01 (0.01); DASH:-0.01 (0.01); HEI:-0.01 (0.01); MeDS:-0.01 (0.01); AHEI:-0.002 (0.01); [underlined: Insulin:] loq-serum insulin, ulU/ml; AHA-DS: −0.02 (0.02); DASH: −0.002 (0.02); HEI: −0.02 (0.02); MeDS:-0.06 (0.02); AHEI: −0.05 (0.02); Summary: Inverse: MeDS, AHEI & log-serum insulin; Null: AHA-DS, DASH, HEI, MeDS, AHEI &HbA1c, serum glucose; AHA-DS, DASH, HEI & log-serum insulin | - Did not account for: None (all); - Diet assessment: FFQ once (baseline); - Outcomes: Fasted (12h+) blood samples for FBG; FBI; HOMA-IR (V2.2.3); - Funding: NIH, NHLBI, NIA
Merino, 2022^97^; USA; HPFS/NHS I, NHS II; Analytic N=35759; Participant characteristics:; - Health: BMI, mean: 24.3-25.5; - In NHS, HPFS, NHS-II: HTN: 15%, 20%, 3%; Dyslipidemia: 8%, 2%, <1%; Family history of diabetes: 30%, 29%, 36%; - Race and/or Ethnicity: ~99% White; - SEP: NR, all health professionals; Selection data: Excluded those without genetic data and with major chronic diseases | Age at Dietary Pattern: 53y [7] NHS, 54y[9]HPFS, 37y[4]NHS-ll; [underlined: DASH score] [Fung, 20081, Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Sodium; [underlined: Alternative HEI (AHEI-2010] [Chiuve 2012], Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol; Methods: Index/Score | Follow-up: ~30y; [underlined: Risk of T2D:]; DASH & T2D; NHS-II, HR: 1.05, 95% CI: 0.97, 1.14; NHS, HR: 1.10, 95% CI: 1.04, 1.17; HPFS, HR: 1.25, 95% CI: 1.16, 1.34; AHEI-2010&T2D; NHS-II, HR: 1.08, 95% CI: 1.00, 1.16; NHS, HR: 1.11, 95% CI: 1.06, 1.17; HPFS, HR: 1.20, 95% CI: 1.12, 1.28; Summary: Inverse: (lower) DASH & (higher) T2D; Inverse: (lower) AHEI-2010 & (higher) T2D | - Did not account for: SEP (health professionals); - Diet assessment: FFQ every 4y, validated; - Outcomes: Self-report confirmed based on criteria: classic symptoms and FPG ≥ 7.8 mmol/L (140 mg/dL; post-2010, 7 mmol/L) or NF ≥ 11.1 mmol/L (200 mg/dL); or no symptoms but 2+ elevated FBG or NF on different occasions or after OGTT; or anti-diabetic agents; or HbA1C ≥ 6.5% post-2010;; - Identified 4433K cases; Analyses examining all participants conducted via meta-analysis (rather than pooled analyses) but found similar results; - Funding: NIH; ADA; National Natural Science Foundation of China
Neuhouser, 2023^98^; USA; Women Health Initiative (WHI); Analytic N=100374; Participant characteristics:; - Health: mean BMI 27.6; - Race and/or Ethnicity: 84.5% White, non-Hispanic 7.7% Black, non-Hispanic; 3.3% Hispanic/Latina; 2.8% Asian/Pacific Islander; - SEP: 42.4% ≥ college degree; Selection data: Excluded those with history of CVD | Age at Dietary Pattern: 63.6y, mean (50 to 79 y); [underlined: HEI-2010,] Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; Fatty Acids. Negative: Refined Grains; Added Sugars in “Empty Calories”; Solid Fats in “Empty Calories”; Sodium; Methods: Index/Score | Follow-up: 22-26y ~; [underlined: Risk of T2D:] HEI-2010 (Uncal per 20%) & T2D risk, HR: 0.91, 95% CI: 0.90, 0.93; HEI-2010 (Cal per 20%) & T2D risk, HR: 0.87, 95% CI: 0.75, 0.99; Summary: Inverse: HEI-2010 (per 20%) & lower risk of T2D | - Did not account for: N/A (all); - Diet assessment: FFQ once (baseline); - Outcomes: Self-report; - Calibration of FFQ HEI-2010 scores attempted to improve properties of self-reported diet and minimize error; Predominantly participants are NHW, so the findings may not be generalizable.; - Funding: NIH/NHLBI
O’Connor, 2020^99^; USA; ARIC; Analytic N=11,991; Participant characteristics:; - Health: BMI, mean: ~26.7-27.6 across quintiles:; - Ob: 21-26%; OW: 37-41% (NSD by Q); - HTN ~30% (NSD by Q); - LDL (mmol/L) ~3.5 (NSD by Q); - Race and/or Ethnicity: ~75% White (no difference across quintiles); - SEP: Higher aMED associated with higher education, by aMED quintile,% completing < HS; HS or =;>HS; - Q1, 26%; 43%; 29%; - Q2, 24%; 41%; 35%; - Q3, 19%; 42%; 39%; - Q4, 15%; 39%; 46%; - Q5, 13%; 38%; 49%; Selection data: Excluded those with history CVD, diabetes, or cancer; implausible energy intake; those identifiying as Asian n=28 or Indian n=14, or as Black from Maryland or Minnesota; missing baseline covariates; LFU; missing food items needed to calculate aMed score | Age at Dietary Pattern: 45 to 65 y at baseline; [underlined: Alternate Med Diet Score (aMED)]; [Fung 2005], Positive: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA/SFA.; Negative: Red and Processed Meat.; Neutral: Alcohol; Methods: Index/Score | Follow-up: 22 y (median); [underlined: Risk of T2D:]; aMED QI, HR: 1, ref; Q2, HR: 1.02, 95% CI: 0.94, 1.11; Q3, HR: 0.89, 95% CI: 0.80, 0.99; Q4, HR: 0.91, 95% CI: 0.81, 1.02; Q5, HR: 0.94, 95% CI: 0.82, 1.07; p-trend=0.03; per 1-pt, HR: 0.98, 95% CI: 0.96, 0.99; Summary: Null: aMED & T2D (categorical); Inverse: aMED & T2D (continuous) | - Did not account for: None (all); - Diet assessment: FFQ at visits 1 and 3; - Outcomes: Combination of self-report of physician diagnosis, use of anti-diabetes meds in past 2 weeks, measured FPG ≥ 126 mg/dl or NFG ≥ 200 mg/dl.; - Funding: NIH, HHS
Otto, 2015^100^; USA; Multi-Ethnic Study of Atherosclerosis (MESA); Analytic N=2505; Participant characteristics:; - Health: 40% OW; 29% Ob; - Race and/or Ethnicity: White: 43%; Black: 25%; Chinese: 11.5%; Hispanic: 21%; - SEP: Some college: ~60-70% of baseline cohort; Selection data: Excluded those with T2D at baseline; unreliable/incomplete/missing data; censored those after age 65y, diagnosis with cancer or CVD | Age at Dietary Pattern: 62y, mean [45 to 84y]; Dietary pattern: Alternative Healthy Eating Index (AHEI) [McCullough 2000]; alternate DASH Score [Appel, 1997] a Priori [Sjitmsa, 2012]:; aHEl: Positive: Vegetables (not potatoes, French fries); Fruit; Nuts and Soy Protein; Cereal Fiber; White: Red Meat Ratio; PUFA:SFA; Multi-Vitamin Use. Negative: Trans-UFA. Neutral: Alcohol; alternate DASH: Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy; Negative: Red and Processed Meat; Sweetened beverages; MUFA+PUFA; Sodium a Priori: Positive: Vegetables-Green; Vegetables-Yellow; Vegetables-Other; Tomatoes; Beans/Legumes; Fruit; Avocado; Nuts, Seeds; Soy Products; Whole Grains; Fish, fatty not fried; Fish, lean not fried; Poultry; Low-Fat Dairy; Beer, Wine, Liquor; Tea, Coffee. Negative: Fried potatoes; High-fat meat; Processed meat; Fried Fish; Fried Poultry; Whole-Fat Dairy; Butter; Candy; Soft drinks; Bakery Desserts; Salty Snacks. Neutral: Potatoes; Fruit Juices; Refined grains; Eggs; Shellfish; Margarine; Chocolate & Diet Soft Drinks; Meal replacements; Pickled foods; Soups, Sugar substitutes; Methods: Index/Score | Follow-up: 5y; [underlined: Risk of T2D]: DASH & T2D, HR: 1.02, 95% CI: 0.79, 1.30; AHEI & T2D, HR: 0.81, 95% CI: 0.65, 1.00; A Priori & T2D, HR: 0.91, 95% CI: 0.71, 1.17; Stronger associations observed in stratification by race/ethnicity in Whites and Chinese Americans, but results attenuated with full adjustment; Summary: NS/Null: DASH, AHEI, or A Priori & T2D | - Did not account for: Family history of diabetes; - Diet assessment: FFQ once (baseline); Imputted missing FFQ data; - Outcomes: Fasted blood samples collected; T2D: FG ≥ 126 mg/dL or new report of diabetes-meds; - Similar results with imputation vs. exclusion of missing values; - Funding:
Pant, 2024^101^; Australia; ALSWH; Analytic N=10006; Participant Characteristic:; Health: mean BMI 26.8 (UPF Q2 & Q3 higher BMI); OW: 21-25% Ob: 16-18%; Normal Wt: 41-46%.; T2D 3-6%; HTN 25-30%; cancer ~3%; PCOS 1%; G DM 3-5%; HRT 32-34%; post-menopause ~25%; (range from UPF quantiles); Race and/or ethnicity: NR SEP:; - No education, 15-17%,; - primary school, 29-33%; - high school; 15-18%; - trade, 3-4%; - diploma, 16-18%; - university degree, 9-10%; - Master or PhD degree 5-7%; - Income, $AU: 6-8% <16K; 50-52% 16K-51,999; 42-43% >51,999; Selection data: Women without CVD and with complete data & plausible FFQ | Dietary pattern at age(s): 52.5y, mean (50 to 55y, third survey year 2001); Nova Classification System [Monteiro, 2019], Group 4 (12 top sources) in rank order: Ready-made meals; Industrial packaged breads; Milk-based drinks; Breakfast cereals; Processed meats; Margarine and other spreads; Industrial potato chips; Processed cakes; Snacks; Ice cream; Biscuits; Confectionary; Dietary pattern Method: Index/Score Analysis | Results at F/U:15 y ~ until 2016; [underlined: Risk of T2D:(Q1,OR: 1 ref)]; - Q2, OR: 1.25, 95% CI: 0.93, 1.68; p=0.14; - Q3, OR: 1.10, 95% CI: 0.81, 1.50; p=0.53; - Q4, OR: 1.08, 95% CI: 0.79, 1.48; p=0.64; - Q5, OR: 1.17, 95% CI: 0.84, 1.63; p=0.35; p-trend=0.74 | - Did not account for: Race/Ethnicity; - Diet assessed once via FFQ; Misclassification possible due to UPF intake based on FFQ as the dietay pattern; - Outcome self-reported T2D; Primary outcome was CVD; - Funding: CAUL and its Member Institutions
Papier, 2019^102^; United Kingdom; EPIC-Oxford Analytic N=45,314; Participant characteristics:; Race and/or Ethnicity: 100% White, European descent (England, Scotland, or Wales); SEP of diet groups:; - % in top SEP quartile: 30%; 25%; 22%; 15%; - % with higher education: 28%; 42%; 46%; 43%; Selection data: Excluded participants who resided outside England, Scotland, or Wales, who did not have an NHS number, hospital admissions or death data, or if they could not be traced by the NHS, or who only completed the short questionnaire, those < 20 y or ≥ 90 y at recruitment, those who did not have any F/U data, participants reporting prevalent cancer except non-melanoma skin cancer, self-reported prior diabetes, heart attack or stroke, participants with unreliable dietary data, with unknown BMI or smoking status. | Age at Dietary Pattern: ≥ 20 y; Mean age at baseline: ~50y (reg meat eaters); ~47y (low meat eaters); ~42y (fish eaters); [underlined: Regular meat eaters]: consuming ≥ 50 g of meat daily; Positive: total, red, and processed meat; animal milk, total energy, added sugar, total and animal protein, and total fat, monounsaturated fat, and saturated fat. Negative: cheese, pulses, nuts, fruit, vegetables, plant protein, total and intrinsic sugar, carbohydrate, fiber, and starch; [underlined: Low meat eaters]: consuming < 50 q of meat daily; Positive: cheese, pulses, nuts, fruit, vegetables, plant protein, total and intrinsic sugar, carbohydrate, fiber, and starch. Negative: total, red, and processed meat; animal milk, total energy, added sugar, total and animal protein, and total fat, monounsaturated fat, and saturated fat.; [underlined: Fish eaters]: consuminq fish but not meat; Positive: cheese, pulses, nuts, fruit, vegetables, plant protein, total and intrinsic sugar, carbohydrate, fiber, and starch. Negative: total, red, and processed meat; animal milk, total energy, added sugar, total and animal protein, and total fat, monounsaturated fat, and saturated fat.; [underlined: Vegetarians]: consuminq dairv products or eggs but not meat or fish; Positive: cheese, pulses, nuts, fruit, vegetables, plant protein, total and intrinsic sugar, carbohydrate, fiber, and starch. Negative: total, red, and processed meat; animal milk, total energy, added sugar, total and animal protein, and total fat, monounsaturated fat, and saturated fat.; [underlined: Vegans]: consuminq no fish, meat, dairy products or eggs; Positive: cheese, pulses, nuts, fruit, vegetables, plant protein, total and intrinsic sugar, carbohydrate, fiber, and starch. Negative: total, red, and processed meat; animal milk, total energy, added sugar, total and animal protein, and total fat, monounsaturated fat, and saturated fat.; Methods: Other: Vegetarian | Follow-up: 17.6 y mean, T2D; [underlined: Risk of T2D]: Reqular meat eaters, HR: 1, ref; Low meat eaters, HR: 0.78, 95% CI: 0.66, 0.92; Fish eaters, HR: 0.64, 95% CI: 0.51, 0.80; Vegetarians, HR: 0.89, 95% CI: 0.76, 1.05; Vegans, HR: 0.99, 95% CI: 0.66, 1.48; p-trend<0.001; Fish vs. Vegetarians, HR: 0.72, 95% CI: 0.56, 0.91; Summary: Inverse: Low-meat eaters, Fish eaters, Vegetarians, Vegans (vs. regular meat) & Lower T2D; Fish (vs. vegetarians) & T2D | - Did not account for: Family history of diabetes; - Diet assessment: FFQ once (baseline); - Outcomes: Health record linkage; - Including energy, carbohydrates, starch, fibre, protein and fat did not change the association between diet groups and diabetes risk; heterogeneity of risk by diet group for BMI but not for age, sex, smoking status, or education level; Underestimate of T2D cases or over-representation of severe diabetes or with co-morbidities; misidentification of hospitalization or death of T2D, diabetes diagnosis time; lack of diabetes medication data for analysis; - Funding: the Wellcome Trust, Our Planet Our Health (Livestock, Environment and People, LEAP); UK Medical Research Council
Pastorino, 2016^103^; United Kingdom; MRC National Survey of Health and Development; Analytic N=1180 at all 3 visits; Age 36: 1804; Age 43: 2267; Age 53: 1478; Participant characteristics:; - Health: BMI, kg/m2: 23.8-27.4; - T2D rate: 6-13%; - Physically inactive: 27-64%; - Current smoker: 6-45%; - Alcohol, g/d: 5.4-12.3; - Race and/or Ethnicity: 100% White British; - SEP (range 36y-53 y), Q1 v. Q5; ○ ‘Manual’ : 21-24% v. 41-45%; ○ No education: 17-42% v. 44-50%; - Selection data: Included data on diet at 36, 43 and 53 years of age and incident T2D diagnosed between 53 and 60-64 years of age. Analyses were restricted to individuals with complete data on diet, as well as all variables needed, and without prevalent diabetes at the age of 53 years. | Age at Dietary Pattern: 36y, 43y and 53y; Dietary pattern: Not named Negative: fruit, vegetables, low-fat dairy products, wholemeal bread, high-fibre cereals; Positive: white bread, fried potatoes, processed meat, butter and animal fat and added sugar; Methods: RRR | Follow-up: age 53, and 60-64 y; [underlined: Risk of T2D]:; ♂ at age 36 y, N=856, Q1, OR: 1, ref; Q2, OR: 1.46, 95% CI: 0.67, 3.18; Q3, OR: 1.23, 95% CI: 0.53, 2.83; Q4, OR: 1.36, 95% CI: 0.59, 3.11; Q5, OR: 1.48, 95% CI: 0.60, 3.66; P for trend=0.51; ♂ at age 43 y, N=1080, Q1, OR: 1, ref; Q2, OR: 0.68, 95% CI: 0.33, 1.40; Q3, OR: 1.23, 95% CI: 0.62, 2.42; Q4, OR: 1.01, 95% CI: 0.49, 2.09; Q5, OR: 1.08, 95% CI: 0.51, 2.28; P for trend=0.55; ♂ at age 53 y, N=669, Q1, OR: 1, ref; Q2, OR: 0.94, 95% CI:0.37, 2.35; Q3, OR: 0.92, 95% CI: 0.37, 2.33; Q4, OR: 1.29, 95% CI: 0.54, 3.06; Q5, OR: 1.58, 95% CI: 0.62, 3.98; P for trend=0.22; ♂ per 1 SD increase, N=524; Change between 36-43 y, OR: 1.09, 95% CI: 0.75, 1.57, P=0.63; Change between 43-53 y, OR: 1.14, 95% CI: 0.80, 1.63, P=0.44; Change between 36-53 y, OR: 1.19, 95% CI: 0.84, 1.68, P=0.30; ♀ at age 36 y, n=948, Q1, OR: 1, ref; Q2, OR: 2.27, 95% CI: 0.93, 5.54; Q3, OR: 2.33, 95% CI: 0.94, 5.78; Q4, OR: 2.53, 95% CI: 1.05, 6.09; Q5, OR: 2.26, 95% CI: 0.83, 6.10; P for trend=0.11,; ♀ at age 43 y, n=1187, Q1, OR: 1, ref; Q2, OR: 1.77, 95% 01:0.61. 5.14; Q3, OR: 3.56, 95% CI: 1.36, 9.35; Q4, OR: 3.77, 95% CI: 1.41, 10.02; Q5, OR: 4.95, 95% CI: 1.77, 13.84; P for trend<0.01; ♀ at age 53 y, n=809, Q1, OR: 1, ref; Q2, OR: 1.94, 95% CI:0.59, 6.49; Q3, OR: 1.64, 95% CI: 0.49, 5.49; Q4, OR: 2.82, 95% CI: 0.89, 8.97; Q5, OR: 2.83, 95% CI: 0.88, 9.09; P for trend=0.05; ♀ per 1 SD increase, N=655; Change between 36-43 y, OR: 1.63, 95% CI: 1.08,2.46, P=0.01; Change between 43-53 y, OR: 1.45, 95% CI: 0.98, 2.15, P=0.05; Change between 36-53 y, OR: 1.65, 95% CI: 1.12,2.42, P=0.01; Summary: Positive: DP & T2D (♀ at age 43 and 53 years); Null: DP & T2D (♀ at age 36, and ♂ all ages) | - Did not account for: Alcohol, Family history of diabetes; - Diet assessment: 5-d diet diary at age 36y, 43y, 53 y; - Outcomes: Self-report at age 53; self-report and FBG at age 60-64; - Interaction between the dietary pattern and sex on T2D was observed at age 43 y (P=0.02); interaction between DP and BMI was not significant (P>0.05). Notable wide variance around effects; Missing data not fully accounted for; - Funding: Medical Research Council
Qiao, 2014^104^; USA; Women Health Initiative (WHI); Analytic N=154,493; Participant characteristics:; - Health: BMI, kg/m2: 27.8 ± 5.8; - Body weight, kg: 73.0 ± 16.6; - WC, cm: 85.9 ±13.5; - PA, MET-hours/week: 12.6 ± 13.8; - Current smoker: 7.0%; - HRT use in last 3 mo: 44%; - Family history of diabetes: 31.0%; - Race and/or Ethnicity: Asian: 2.6%; - Black: 8.3%; - Hispanic: 3.9; - White: 83.7%; - SEP: Education; - < High school: 5.1%; - High school/GED: 17.0%; - > High school, < 4 y college: 37.8%; - ≥4 y college: 40.1%; Selection data: Included postmenopausal ♀ age 50 to 79y, able to complete study visits, and an expected survival and residency for at least 3 y. Excluded those with current alcoholism, drug dependency, dementia, or other conditions that would limit full participation, and missing data and prevalent cases of diabetes at baseline or a history of gestational diabetes. | Age at Dietary Pattern: 63y, mean (50 to 79 y); [underlined: Alternative Healthv Eatinq Index (AHEI)] [McCullouqh 20001, Positive: Vegetables (not potatoes, French fries); Fruit; Nuts and Soy Protein; Total Dietary Fiber; White: Red Meat Ratio; PUFA:SFA; Multi-Vitamin Use. Negative: Trans-UFA. Neutral: Alcohol; Methods: Index/Score | Follow-up: 7.6 y mean, T2D; [underlined: Risk of T2D]:Q1, HR 1, ref; Q2, HR 0.92, 95% CI: 0.87, 0.98; Q3, HR 0.88, 95% CI: 0.82, 0.93; Q4, HR 0.80, 95% CI: 0.74, 0.86; Q5, HR 0.76, 95% CI: 0.70, 0.82; Whites; Q2, HR 0.90, 95% CI: 0.84, 0.97; Q3, HR 0.84, 95% CI: 0.78, 0.91; Q4, HR 0.75, 95% CI: 0.69, 0.82; Q5, HR 0.74, 95% CI: 0.68, 0.82; Blacks; Q2, HR 1.03, 95% CI: 0.90, 1.20; Q3, HR 1.01, 95% CI: 0.86, 1.19; Q4, HR 1.01, 95% CI: 0.85, 1.21; Q5, HR 0.85, 95% CI: 0.69, 1.05; Hispanics; Q2, HR 0.98, 95% CI: 0.79, 1.23; Q3, HR 0.97, 95% CI: 0.75, 1.24; Q4, HR 0.70, 95% CI: 0.52, 0.96; Q5, HR 0.68, 95% CI: 0.46, 0.99; Asians; Q2, HR 1.02, 95% CI: 0.68, 1.53; Q3, HR 0.91, 95% CI: 0.60, 1.39; Q4, HR 1.24, 95% CI: 0.82, 1.87; Q5, HR 0.88, 95% CI: 0.57, 1.38; Summary: Inverse: Higher AHEI & lower T2D overall, among whites & Hispanics; Null: AHEI & T2D among Blacks & Asians | - Did not account for: None (all); - Diet assessment: FFQ once (baseline); - Outcomes: Self-report of diabetes; accuracy assessed using medication and lab data; - Funding: NHLBI; NIDDK; Umass Diabetes and Endocrinology Research Center; U.S. Department of Health and Human Services
Rajaobelina, 2019^105^; France; E3N; Analytic N=72,655; Participant characteristics:; - Health: BMI<25kg/m2: 80.4%; 25-30 kg/m2: 16.3%; ≥30 kg/m2: 3.4%; ○ Tobacco smoker: 13.5%; ○ PA: >20 MET-h/wk: 79.9%;; ○ HTN: 51.7%; HC 7.1%; ○ Family history of diabetes: 11.1%; ○ Premenopausal: 41.1%; ○ Menopausal and no hormone therapy: 29.6%; - Race and/or Ethnicity: NR (French); - SEP: Deprivation index:; ○ < 0.80: 24.1%; ○ 0.80 and--0.12:22.6%; ○ 0.13 and 0.43: 24.1%; ○ >0.43:23.5%; - Education level: <HS diploma: 11.3%; Up to 2 y of university: 53.0%; >2 y of university: 35.7%; # of children: 2.0 ± 1.2; Selection data: Included ♀ with dietary information available in 1993. Excluded those who did not complete F/U after the dietary questionnaire, and those with pre-existing diabetes at the time of the dietary questionnaire. | Age at Dietary Pattern: 53 [7] y; [underlined: Mediterranean Diet Score (MDS)] modified [Hodge 2011], Positive: Vegetables; Legumes; Fruit, Nuts; Cereals; Fish and Seafood; Olive Oil. Negative: Red and Processed Meat; Dairy Products (milk, yogurt, cheese). Neutral: Alcohol; Methods: Index/Score | Follow-up: 0~18 y, T2D; Risk of T2D: MDS 4-5, HR: 1.08, 95% CI: 0.94, 1.24, P=0.27 MDS 0-3, HR: 1.26, 95% CI: 1.10, 1.44, P=0.001 Summary: Inverse: MDS & T2D | - Did not account for: Race and/or ethnicity,; - Diet assessment: Questionnaire once (validated); - Outcomes: Combination of self-report before 2004 or insurance reimbursement (after 2004); - ‘Western’ diet derived from a posteriori methods not described; - Funding: the Mutuelle Générale de l’Education Nationale, European Community, French League Against Cancer, Gustave Roussy, and the French Institute of Health and Medical Research; French Research Agency; Paris-Saclay University
Rayner, 2020^106^; Australia; Australian Longitudinal Study on Women’s Health; Analytic N=9689; Participant characteristics:; - Health: Across LCD quantiles:; - GDM history: 3.5%; - PA: low 52-59%; moderate 18-23%; high: 23-26%; - BMI, <25; 25-30≥30 kg/m2: 41-52%; ~31-34%; 16-25%; - Race and/or Ethnicity: NR (Birth country: Australia: 67-77%; Europe/English-speaking country: 20-27%; Asia: 3-6%); - SEP: Highest education, no formal: 13-15%, high school certificate: 44-50%, trade/diploma: 20-22%, university degree: 16-20%; - Employment status, unemployed: 20-23%, Part-time: 26-37%, Full-time: 42-45%; Area of residence, Urban: 67-73%; - Selection data: Women from 1946-51 cohort, survey of Australian ♀.; Excluded ♀ who reported T1D or T2D prior to 2001, extreme energy intakes (top and bottom 2.5%), and missing dietary data | Age at Dietary Pattern: 50 to 55 y; [underlined: Low-carbohvdrate diet score,] Positive: energy intake from fat and protein; total fat; saturated fat; MUFA; PUFA; vegetables; white bread. Negative: energy intake from carb; dietary fiber; total sugar; fruit; fruit juice; cereal; high-fibre bread; pasta and rice; discretionary foods; added sugar; Methods: Index/Score | Follow-up: 15 y, T2D; [underlined: Risk of T2D]:; Q1 (least restricted/higher carb): RR 1, ref; Q2: RR 0.95, 95% CI: 0.81, 1.10; Q3: RR 1.06, 95% CI: 0.89, 1.26; Q4: RR 1.10, 95% CI: 0.95, 1.27; P trend=0.03; (fully adjusted model); Summary: Positive: carbohydrate restriction & T2D | - Did not account for: Race and/or ethnicity (birth country adjusted); - Diet assessment: FFQ at 2001 and 2013 visits; - Outcomes: Self-report with validation and strong agreement with hospital records, k=0.75.; - Self-reported GDM that has not been validated.; - Funding: Australian Government Department of Health
Riboldi, 2022^107^; Brazil; ELSA-Brasil; Analytic N=9909; Participant characteristics:; - Health: BMI, kg/m2: 25.8, 23.3-28.6; - WC, cm: Men: 92.9, 86.2-100.0; Women: 84.3, 77.4-92.4; - WHR: Men 0.94, 0.89-0.98; Women 0.83, 0.79-0.88; - Many additional markers reported (e.g., BP, HbA1c, lipids, etc.); - Race and/or Ethnicity: 14.42% Black, 27.7% Brown, 54.5% White; - SEP: NR; Selection data: Excluded those with chronic disease, using warfarin, undergone bariatric surgery, incomplete FFQ, implausible/extreme intake, missing covariates or data on diabetes | Age at Dietary Pattern: 50 y, median (35 to 74 y); [underlined: Inflammatory Food Index (IFI)]; [Roboldi, 2022], Positive: Hot dogs; Processed meat; Red meat; Pork; Seafood; Diet soda; Soda; Coffee with sugar; Juice (artificial with sugar); Juice (artificial without sugar); Beer Negative:Butter; Nuts; Wine; Pizza; Chicken meat; Fruits; Whole-grain cereal; Methods: Index/Score | Follow-up: 3.7 y; [underlined: Risk of T2D]: T1,OR: 1, ref; T2, OR: 1.11, 95% CI: 0.92, 1.34; T3, OR: 1.03, 95% CI: 0.85, 1.25; cont, OR: 1.04, 95% CI: 0.96, 1.12; Summary: Null: IFI scores & T2D | - Did not account for: N/A (all); - Diet assessment: FFQ once (baseline); - Outcomes: Fasted (8-15h) blood samples collected; T2D via self-report or measured FPG ≥ 126 mg/dl, or 2-h post 75-g glucose load ≥ 200 mg/dl, or HbA1C ≥ 6.5%; - Secondary analyses adjusted for baseline WC instead of BMI, dieting between visits, or removing alcohol produced similar results; - Funding: Ministry of Health (Department of Science and Technology), Ministry of Science and Technology (Financier of Studies and Projects and National Research Council)
Ruiz-Estigarribia, 2020^108^; Spain; Seguimiento Universidad de Navarra (SUN) cohort; Analytic N=11,005; Participant characteristics:; - Health: By HLS 0-4; 5-6; 7-9:; - HC: 20.4%; 20.7%; 17.6%; - HTG: 9.3%; 8.8%; 7.5%; - Race and/or Ethnicity: NR; - SEP: Martial status by Healthy Lifestyle Score; - 0-4, single: 34.8%; married: 59.6%; other: 5.6%; - 5-6, single: 36.9%; married: 57.4%; other: 5.7%; - 7-9, single: 40.4%; married: 53.9%; other: 5.7%; - University Education by Healthy lifestyle Score (mean); - HLS 0-4, 5.0y; - HLS 5-6, 5.2y; - HLS 7-9, 5.3y; Selection data: Excluded those with baseline BMI <22; with T2D, GDM, CVD, cancer at baseline; extreme TEI | Age at Dietary Pattern: 40.2 y at baseline; [underlined: Mediterranean Diet Score (MDS)]; [Trichopolou 2003], Positive: Vegetables; Legumes; Fruit, Nuts; Cereals; Fish; MUFA/SFA. Negative: Red and Processed Meat; Dairy Products. Alcohol excluded (considered separately); Methods: Index/Score | Follow-up: 12 y (median); [underlined: Risk of T2D]: MDS ≥4 vs. <4 & T2D, HR: 0.70, 95% CI: 0.50, 0.99; Summary: Inverse: MDS & T2D | - Did not account for: Race and/or ethnicity; Alcohol (NSD); - Diet assessment: FFQ once (baseline); - Outcomes: Self-report of T2D or from use of oral anti-diabetes meds at any F/U; - Notably large effect size but relatively few cases (Identified 145 cases); Large portion excluded for BMI < 22 (7K+); MDS & T2D relationship examined indirectly as study aim was Lifestyle Score (HLS) & T2D; - Funding: Spanish Government-Institute of Health Carlos III, European Regional Development Fund, CIBERobn, Navarra Regional Government, University of Navarra
Sali, 2020^109^; Iran; Tehran Lipid and Glucose Study (TLGS); Analytic N=4356; Participant characteristics:; - Health: LCS Q1-Q5:; - HTN, 15.8%, 14.0%, 12.3%, 13.8%; p-trend=0.025; - FBG (mg/dL), 93.1 , 92.7, 92.2, 92.1; p=0.015; - Race and/or Ethnicity: NR (Iranian); - SEP: High education level: 68.7-71.1%(no diff by quartile LCS); Selection data: Excluded those with a history of myocardial infarction, stroke, or cancer; who reported extreme TEI; those on specific diets; those pregnant or lactating; LFU | Age at Dietary Pattern: 40.5y mean (≥19y at baseline); [underlined: Low Carbohydrate Diet Score (LCD)]; [Halton, 2008]:; LCD: Positive: vegetables, legumes & nuts, dairy, red & processed meat. Negative: fruits, refined grains, whole grains; LCD-animal: Positive: animal protein, animal fat; LCD-vegetable: Positive: vegetable protein, vegetable fat; Methods: Index/Score | Follow-up: 3 y; [underlined: Risk of T2D]:Q1,OR: 1, ref; LCD; Q2, OR: 1.50, 95% CI: 0.89, 2.52; Q3, OR: 1.26, 95% CI: 0.67, 2.34; Q4, OR: 2.16, 95% CI: 1.16, 4.04; p-trend=0.015; LCD- animal; Q2, OR: 1.59, 95% CI: 0.93, 2.72; Q3, OR: 1.25, 95% CI: 0.70, 2.24; Q4, OR: 1.81, 95% CI: 1.06, 3.11; p-trend=0.029; LCD - veg; Q2, OR: 1.14, 95% CI: 0.66, 1.95; Q3, OR: 1.30, 95% CI: 0.75, 2.22; Q4, OR: 1.47, 95% CI: 0.85, 2.52; p-trend=0.160; Summary: Positive: LCD or LCD-animal & T2D; NS/Positive: LCD-veg &T2D | - Did not account for: Race/Ethnicity (Iranian), Alcohol (not consumed); - Diet assessment: FFQ once (baseline); - Outcomes: Fasted blood samples and 2h OGTT collected; T2D based on ADA: FPG ≥ 126 mg/dl or 2-h post 75-g glucose load ≥ 200 mg/dl or use of anti-diabetes meds; - Larger effect sizes but wide CI; Indirectly examining dietary patterns with LCD scores focused on macronutrients; Foods described are based on dietary intakes by quartile of LCD score; - Funding: Shahid Beheshti University of Medical Sciences
Satija, 2016^110^; USA; NHS, NHS II, HPFS; Analytic N=69949, NHS I; 90239; NHS-II; 40539 HPFS; Participant characteristics:; - Health: NHS I; NHS-II; HPFS; - Current smoker: 19-28%; 10-14%; 5-13%; - PA, MET-h/wk: 11-20; 16-30; 18-29; - BMI, kg/m2: 24-25; 24-25; 25-26; - Family history of diabetes: ~28%; 33-35%; ~21%; - HTN history: ~7%; 5-8%; 17-19%; - HC history: 2-5%; 14-15%; 7-15%; - Alcohol use, g/d: 6-7; ~3; 11-12; - Premenopausal ~32-61%; 48-98%; - HRT use: ~3%; - Race and/or Ethnicity: 95-99% White; - SEP: NR, all health professionals; Selection data: Excluded participants with diabetes, cancer (except nonmelanoma skin cancer), CVD, extreme TEI or incomplete dietary data at baseline | Age at Dietary Pattern: 50y, mean (NHS: 38 to 63 y); 36y, mean (NHS 2: 27 to 44 y); 53y, mean (HPFS: 40 to 75 y); [underlined: Plant-Based Diet Index (PDI) [Satiia, 2016]], Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Negative: Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; [underlined: Healthful PDI (hPDI)], Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Negative: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; [underlined: unhealthful PDI (uPDI),] Negative: Whole grains; Fruits; Vegetables; Nuts; Legumes; Vegetable oils; Tea/coffee; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; Positive: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Methods: Index/Score | Follow-up: NHS: 28 y; NHS 2: 20 y; HPFS: 24 y(inffered); [underlined: Risk of T2D]: D1, HR: 1, ref; PDI, Pooled; D2, HR: 0.99, 95% CI: 0.93, 1.05; D3, HR: 0.92, 95% CI: 0.86, 0.98; D4, HR: 0.93, 95% CI: 0.87, 0.99; D5, HR: 0.92, 95% CI: 0.86, 0.99; D6, HR: 0.86, 95% CI: 0.80, 0.92; D7, HR: 0.91, 95% CI: 0.85, 0.98; D8, HR: 0.82, 95% CI: 0.76, 0.88; D9, HR: 0.88, 95% CI: 0.82, 0.94; D10, HR: 0.81, 95% CI: 0.75, 0.88; Per 10 units, HR: 0.89, 95% CI: 0.86, 0.92,; P for trend<0.001; hPDI, Pooled; D2, HR: 0.99, 95% Cl: 0.93, 1.05; D3, HR: 0.90, 95% Cl: 0.85, 0.96; D4, HR: 0.87, 95% Cl: 0.81, 0.93; D5, HR: 0.82, 95% Cl: 0.77, 0.88; D6, HR: 0.83, 95% Cl: 0.77, 0.88; D7, HR: 0.82, 95% Cl: 0.77, 0.88; D8, HR: 0.75, 95% Cl: 0.70, 0.81; D9, HR: 0.73, 95% Cl: 0.68, 0.79; D10, HR: 0.66, 95% Cl: 0.61, 0.71; Per 10 units, HR: 0.82, 95% Cl: 0.80, 0.85,; P for trend<0.001; (Data NR for uPDI); Summary: Inverse: Higher PDI, hPDI & lower T2D | - Did not account for: Sex (pooled analysis); - Diet assessment: FFQ every 2-4y; - Outcomes: Self-report confirmed with reported f/u based on NDDG criteria: classic symptoms and FPG ≥ 7.8 mmol/L (140 mg/dL; post-2010, 7 mmol/L) or NF ≥ 11.1 mmol/L (200 mg/dL); or no symptoms but 2+ elevated FBG or NF on different occasions or after OGTT; or Tx with anti-diabetes agents; or HbA1C ≥ 6.5% post-2010; - Stratification by physical activity and family history yielded similar results for PDI and hPDI; inverse association was stronger in non-obese than in obese for PDI, and in older than younger for PDI and hPDI; no effect modification of ethnicity;; - Resuts for PDI and hPDI did not change upon adjustment for ethnicity, marital status, recent physical exam, diet beverage intake, and other SEP indicators; when restricting to participants with FPG in previous 2y; when continuously updating PDI and hPDI throughout follow-up; or when adjusting Mediterranean diet in the model. Associations were modestly attenuated when using baseline intakes of PDI and hPDI; or when using the most recent diet scores prior to diagnosis of T2D; or when adjusting aHEl or DASH.; - Funding: NIH
Seah, 2019^111^; Singapore; Singapore Chinese Health Study; Analytic N=45,411; Participant characteristics:; - BMI, kg/m2: 22.9-23.2; - Current smokers: 11-38%; - Physically active: 9-14%; - History of HTN 18-25% or diabetes: 5-10%; - Alcohol intake, g/d: 0.9-5.4; - Race and/or ethnicity: Cantonese-speaking: 42.8% to 51.8%; - SEP: Higher education Q1 : 23.6%; Q2: 24.3%; Q3: 26.7%; Q4: 30.5%; Q5: 38.2%; Selection data: Recruited participants who lived in Singapore government-built housing estates. Used data from control participants without CVD or stroke who provided blood samples; Excluded participants without data/nonresponders; who had diabetes, cancer, or CVD at baseline or implausible TEI for analyses | Age at Dietary Pattern: 56y, 45 to 74y; Dietary pattern, Positive: soy, vegetables (dark green, light green, preserved, yellow), fruits, tea, tomato products, bread, fish, margarine and dairy. Negative: rice, fresh red meat, coffee, alcohol, organ red meat, sugar-sweetened beverages, and eggs.; Methods: RRR | Follow-up: 11 y mean T2D; [underlined: Risk of T2D]:; ♂ & ♀, Q1, HR: 1, ref; Q2, HR: 1.01, 95% CI: 0.93, 1.10; Q3, HR: 0.99, 95% CI: 0.91, 1.08; Q4, HR: 0.89, 95% CI: 0.81, 0.97; Q5, HR: 0.86, 95% Cl: 0.79, 0.95; P-trend<0.001; ♂, Q1 ref; Q2, HR: 1.01, 95% Cl: 0.90, 1.15; Q3, HR: 0.95, 95% Cl: 0.83, 1.08; Q4, HR: 0.93, 95% Cl: 0.81, 1.06; Q5, HR: 0.93, 95% Cl: 0.81, 1.06; P-trend=0.157; ♀,Q1 ref; Q2, HR: 1.00, 95% Cl: 0.88, 1.13; Q3, HR: 1.00, 95% Cl: 0.88, 1.13; Q4, HR: 0.86, 95% Cl: 0.76, 0.97; Q5, HR: 0.81, 95% Cl: 0.72, 0.93; P-trend<0.001; Summary: Inverse: Dietary pattern in ♀, ♂, or ♀+ ♂ & T2D | - Did not account for: Race/Ethnicity (Chinese and adjusted dialect group); Family history of diabetes; - Diet assessment: FFQ once; validated and referenced with sub-set of 24h recalls; - Outcomes: Self-report and validated; - No effect modification by sex, age, overweight status, diabetes history was observed.; - Limitations: potential underdiagnosis of diabetes; cooking methods infomation was not used; - Funding: NIH; National University of Singapore Graduate School for Integrative Sciences and Engineering; NationalMedical Research Council, Singapore
Shah, 2021^112^; France; E3N; Analytic N=70,991; Participant characteristics:; - Health: BMI <20 kg/m2: 14.45%; ≥ 20-24 kg/m2: 66.03%; - Family history of diabetes: 11.10%; - HC: 7.09%; - Smoking status, current: 13.5%; Past: 32.8%; - PA, MET-h/week: 50.48%; - Race and/or Ethnicity: NR (French); - SEP: Educational level, <BS/BA: 11%; BS/BA+2: 53%; > BS/BA and BS/BA+2: 36%; Selection data: Eligible ♀ completed and returned the baseline dietary questionnaire sent in 1993.; Excluded those with extreme TEI, ♀ who did not complete any F/U after the FFQ; who had T2D and HTN before current study baseline for respective analyses | Age at Dietary Pattern: 40 to 65 y, mean: 53 [7] y; [underlined: Paleolithic Score [Whalen 2014],]; Positive: Vegetables; Fruit and Vegetable Diversity; Fruit; Nuts; Fish; Lean Meat; Calcium (from non-dairy foods). Negative: Grains and Starches; Baked Goods; Red and Processed Meat; Dairy Foods; Alcohol; Sodium; Methods: Index/Score | Follow-up: 18.81 y mean [SD 4.3], T2D; [underlined: Risk of T2D]:; Q1, HR: 1, ref; Q2, HR: 0.91, 95% Cl: 0.82, 1.02; Q3, HR: 0.87, 95% Cl: 0.77, 0.98; Q4, HR: 0.94, 95% Cl: 0.84, 1.05; Q5, HR: 0.88, 95% Cl: 0.79, 0.98; P-trend<0.0001; Per 1-SD, HR: 0.96, 95% CI: 0.93, 1.00; Summary: Inverse: Paleolithic Score & T2D | - Did not account for: Race and/or ethnicity,; - Diet assessment: FFQ once; - Outcomes: Combination of self-report (questionnaire) or drug reimbursement databases (only from drug reimbursement after 2004); - Excluding T2D and HTN diagnosed in the first 5 years of follow-up or further adjustment of Western diet did not substantially change results.; - Limitations: unaccounted confounding; caution with generalization - limited to ♀ with relatively higher education level and health awareness; - Funding: IDEX Paris Saclay, the Nutriperso Project; the Mutuelle Générale de l’éducation Nationale, the Institut GUSTAVE ROUSSY and the Ligue contre le Cancer; the National Research Agency. “Investissement d’avenir”; “Ministère de l’enseignement supérieur, de la r
Shan, 2018^113^; USA; NHS, NHS 2; Analytic N=143410 (NHSI: 55324; NHSII: 88086); Participant characteristics:; - Health: BMI, kg/m2: 25.1-26.4; - Alcohol intake, g/d: 6.2 ± 10.7; - PA, Moderate/vigorous, h/wk: 1.9-2.6; - Current smoker: 11-23%; - Postmenopausal:; ○ 70-74% NHSI; 3-4% NHSII; - Family history of diabetes:; ○ 28-31% NHSI; 15-19% NHSII; - Alcohol intake, g/d: ~ 3-6.4; - Race and/or Ethnicity: 95-98% White ‘ethnicity’; - SEP:; ○ Married:~69-81%; ○ Living alone: ~7-12%; Selection data: Excluded participants with diabetes, CVD, or cancer at baseline, missing data on shift work or covariates (age, diet, physical activity, smoking status, or body weight). | Age at Dietary Pattern: 54y, mean NHS: 42 to 67 y; 36y, mean NHSII: 27 to 44 y; [underlined: Alternative HEI (AHED-2010 [Chiuve 2012],] Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol; Methods: Index/Score | Follow-up: 22-24 y T2D; [underlined: Risk of T2D]: NHS, Q1, HR 1, ref; Q2, HR 0.95, 95% CI: 0.88, 1.03; Q3, HR 0.93, 95% CI: 0.86, 1.01; Q4, HR 0.91, 95% CI: 0.84, 0.99; Q5, HR 0.80, 95% CI: 0.73, 0.87; Q1-3 vs. Q4-5, HR: 1.16, 95% CI: 1.10, 1.23; NHS2, Q1,HR1,ref; Q2, HR 0.99, 95% CI: 0.92, 1.07; Q3, HR 0.88, 95% CI: 0.81, 0.96; Q4, HR 0.89, 95% CI: 0.82, 0.97; Q5, HR 0.83, 95% CI: 0.76, 0.91; Q1-3 vs. Q4-5, HR: 1.24, 95% CI: 1.17, 1.32; Pooled NHS1 & NHS2, Q1, HR 1, ref; Q2, HR 0.97, 95% CI: 0.92, 1.03; Q3, HR 0.91, 95% CI: 0.86, 0.96; Q4, HR 0.90, 95% CI: 0.85, 0.96; Q5, HR 0.81, 95% CI: 0.76, 0.87; Q1-3 vs. Q4-5, HR: 1.20, 95% CI: 1.13, 1.28; Summary: Inverse: AHEI & T2D | - Did not account for: SEP (but all health professionals, marital and living status were adjusted); - Diet assessment: FFQ every 4y; - Outcomes: Self-report of diagnosis with supplementary validation questionnaire and validation in subsample; - Association with diet was not the primary interest of the study;; - Other common limitations: limited generalizibility; misclassification bias due to measurement error; residual confounding; - Funding: NIH; Young Scientists Fund of the National Natural Science Foundation of China; the China Postdoctoral Science Foundation;
Song, 2018^114^; Korea; KOGES; Analytic N=5097 (♂ 2410; ♀ 2687); Participant characteristics:; - Health: Men; Women; - BMI, kg/m2: ~24; 24-25; - PA, METs h/wk: 8.1-9.7-; 6.7-11.7; - Smoking status, Current: 40-52%; 2-3%, Past: 27-36%;~1%; - Alcohol use, Current: 71-73%; 24-29%; - Family history of diabetes: ~10%; 10-13%; - Race and/or Ethnicity: NR (Korean); - SEP: Residential area, Rural; ○ Men,~31% to 54%; ○ Women, ~37% to 70%; Selection data: Excluded at baseline, participants: with diabetes, cancer, CVD; missing data on relevant information; Tx for diabetes or stroke with meds; who did not have baseline FBG, OGTT, or HbAIC, or who met ADA criteria for diabetes; who did not have serum TG or HDL, or outlier values for TG or HDL-C (n=4). Excluded individuals who did not answer, had 12+ blanks or missing rice/alcohole intake on FFQs, extreme/implausible dietary intakes; who were not followed at the 5th or 6th visit or unknown diabetes at F/U. | Age at Dietary Pattern: 50y, mean (40 to 69 y at baseline); ♂ Positive: noodles, fruits, fermented salted seafood. Negative: candy and chocolate, nuts, and pork; ♀ Positive: organ and other meats. Negative: dairy products and nuts.; Methods: RRR | Follow-up: 11.54 y mean T2D; [underlined: Risk of T2D]:Q1,OR: 1,ref; ♂; Q2, OR: 1.16, 95% CI: 0.84, 1.59; Q3, OR: 1.08, 95% CI: 0.78, 1.49; Q4, OR: 1.12, 95% CI: 0.82, 1.53; Q5, OR: 1.48, 95% CI: 1.09, 2.03; P trend=0.019; ♀; Q2, OR: 0.80, 95% CI: 0.57, 1.13; Q3, OR: 1.37, 95% CI: 1.00, 1.89; Q4, OR: 1.14, 95% CI: 0.81, 1.59; Q5, OR: 1.21, 95% CI: 0.86, 1.70; P trend=0.053; Summary: Positive: Dietary pattern &T2D | - Did not account for: Race and/or ethnicity (100% Korean); - Diet assessment: FFQ once (baseline); - Outcomes: Fasted (8h+) blood samples collected; T2D via measured FPG ≥ 126 mg/dl, 1-h or 2-h post 75-g glucose load ≥ 200 mg/dl, or HbAIC ≥ 6.5%, or reported T2D diagnosis or on anti-diabetes meds; - Risks before adjusting BMI, ♂ Q2: OR 1.17, 95% CI: 0.85, 1.61; Q3: OR 1.12, 95% CI: 0.81, 1.54; Q4: 1.19, 95% CI: 0.87, 1.63; Q5: 1.53, 95% CI: 1.12,2.09, P trend=0.008; ♀: Q2: OR 0.83, 95% CI: 0.59, 1.16; Q3: OR 1.45, 95% CI: 1.06, 1.99; Q4: 1.23, 95% CI: 0.88, 1.71; Q5: 1.33, 95% CI: 0.95, 1.86, P=0.011;; - Missing ~20% data on T2D incidence; - Funding: Korea Ministry of Science and ICT, National Research Foundation of Korea, Support Program for Women in Science, Engineering and Technology
Song, 2021^115^; United Kingdom; BIOBANK; Analytic N=54274 (Diet & T2D) 430971 (total); Participant characteristics:; - Health: NR; - Race and/or Ethnicity: 96.8% White; - SEP: SES Quintiles: ~ 20-33% most deprived; ~14-20% least deprived, ~53-60% middle; Education ~24 to 35% higher than upper secondary; Selection data: Excluded those with diabetes or cancer before/at baseline or had missing data. | Age at Dietary Pattern: 56y, mean (37 to 73y); [underlined: hiqh-qualitv^1^ diet score [Sonq, 2021],]; Positive: Fruit, Vegetable, Fish/Shellfish; Negative: Processed meats; Neutral/Negative: Unprocessed meats;; Methods: Index/Score | Follow-up: 8.6y; [underlined: Risk of T2D]: Diet score & T2D, HR: 0.90, 95% CI: 0.82, 0.99; Risk diff. 9.66%; PAR%, 8.69, 95% CI: 0.71, 16.03; Summary: Inverse: ‘high-quality’ (top 2/5th) diet score & T2D | - Did not account for: Alcohol (co-Exposure for HLS), Race/Ethnicity, Anthropometry (BMI, co-Exposure for HLS); - Diet assessment: data NR (presume once via FFQ); - Outcomes: T2D from hospital records; - Primary aim was to examine composite HLS, focuse on sleep in relation to T2D; data reported differently in abstract vs. results (~12K vs. 6.9K T2D cases; n=54K vs. 430K); - Funding: National Key R&D Program of China, the Peking University Start-up Grant, High-performance Computing Platform of Peking University, and the China-Canada Key Lab of Nutrition and Health at Beijing Technology and Business University
Srour, 2020^116^; France; NutriNet-Santé Cohort; Analytic N=104707; Participant characteristics:; - Health: Smoking, Current: 17%, Former: 33%; - PA, IPAQ high: 28.1%, moderate: 37%; - BMI <25 kg/m2: 69.1%; 25-29.9 kg/m2: 20%; - Race and/or Ethnicity: NR (French); - SEP: Eudcational level, < High school degree: 17.14%; - Educational level, < 2 y after high school: 17.08%; - Education level ≥2 y after high school: 59.39%; - Selection data: Included participants with>2 dietary records before Janurary, 2017; Excluded participants with underreported energy intake, who have prevalent or incident T1D or prevalent T2D | Age at Dietary Pattern: 42.7 [14.5] y, mean (baseline ≥ 18 y); [underlined: Nova Classification System [Monteiro, 20161, Group 4 “Ultra-processed food” (UPF, Nova 4),] Positive: Suqarv drinks (e.g. regular sodas, sugary fruit-based beverages, industrial chocolate powder beverages, energy drinks, flavoured waters); artificially sweetened beverages (e.g. diet sodas, artificially sweetened ice teas); Flavoured or artificially sweetened yoghurts; products such as dairy desserts, cream cheese, milkshakes, dairy beverages, flavoured milk with one or more texturizer, emulsifier, colorant or other cosmetic additives; Sauces and dressings (salad dressing, mayonnaise, ketchup, béchamel, and other dressings) containing emulsifiers, texturizers, flavour enhancers or other additives; instant powder soups; reconstituted vegetarian/soy steaks with additives; flavoured and artificially sweetened fruit compotes; vegan nuggets; Processed meat with added nitrites; chicken nuggets; fish fingers; industrial ‘cordon bleu’ chicken with wheat dextrose, emulsifiers, preservatives; surimi-crab sticks; Flavoured breakfast cereals with added emulsifiers, texturizing agents and/or colorants; industrial pre-baked breads and buns with added dextrose, preservatives or emulsifiers; Industrially packed cookies, cakes, chocolate/wafer bars, and candies manufactured with glucose syrup, modified starch, hydrogenated oils, colours, flavours; Chips, crisps and crackers made with other ingredients than potatoes, oil and salt such as maltodextrin, flavors, dyes, emulsifiers, flavour enhancers; Methods: Index/Score | Follow-up: 6.0 y median, T2D; [underlined: Risk of T2D]:; Per 10% increase Nova 4, HR: 1.15, 95% CI: 1.06, 1.25, P-value=0.001; Per 100 g/d increase Nova 4 (adjusting for non-Nova 4), HR: 1.05, 95% CI: 1.02, 1.08, P-value=0.003; Per 10% increase Nova 1+ 2, HR: 0.91, 95% CI: 0.84, 0.98; P=0.01; Summary: Positive: UPF (Nova 4) & T2D; Inverse: Non-UPF (non-Nova 4) & T2D | - Did not account for: Race and/or ethnicity (all French); - Diet assessment: 24-h records at baseline and every 6 months (>3 nonconsecutive, validated, web-based); - Outcomes: Self-report, confirmed by health insurance; subsample via biomarker; - Additional model results for 10% increment of UPF, further adjusting baseline prevalent dyslipidemia and hypertension, and treatments for these conditions: HR 1.13, 95% CI: 1.03, 1.23, P=0.006; adjusting percentage of weight change: HR 1.13, 95% CI: 1.01, 1.27, P=0.04. Sensitivity analyses showed no substantial difference from the major results.; - Limitations: potential underreport of T2D cases, residual confounding, misclassification of Nova , nonrepresentative sample of the general population.; - Funding: Ministère de la Santé, Santé Publique France, Institut National de la Santé et de la Recherche Médicale. Institut National de la Recherche Agronomique, Conservatoire National des Arts etMétiers and Université Paris 13
Tait, 2020^117^; Canada; Canadian Community Health Survey; Analytic N=4755; Participant characteristics:; - Health: OW: 31-32%; - Smoker: Current: 10-44%, Former: 23-27%; - Alcohol use: Non: 12-29%, Occasional: 32-39%, Regular: 33-38%; - PA: inactive: 51-56%, moderate: 25-32%, active: 19-23%; - Race and/or Ethnicity: 68.7%-88.6% Caucasian; - SEP: HEI-Canadian quantiles ranged in Income quantile from 12-24%; Selection data: Included Ontario respondents in CCHS Cycle 2.2, among whom gave permission to share information on demographic characteristics, health behaviors, medical histories, and 24-h dietary recall and whose infomation linked successfully with administrative health database for diabetes registry. Excluded individuals < 18 y at baseline, pregnant ♀, prevalent case of diabetes before respondents’ 2004 CCHS interview date and underweight individuals | Age at Dietary Pattern: >18 y; [underlined: Healthv Eatinq Index via Candadian Food Guide (HEI-C) [Tait. 2020],]; Positive: Total Vegetables and Fruit; Dark Green, Orange Vegetables; Whole Fruit; Total Grains; Whole Grains; Milk/Milk alt.; Meat/Meat alt.; USFA. Negative/Neutral: SFA; Sodium; Other” foods; Methods: Index/Score | Follow-up: 12.1 y max; [underlined: Risk of T2D]: adjusted for BMI, Q1 : HR 1, ref; Pooled:; Q2: HR 0.69, 95% CI: 0.44, 1.08, P=0.687; Q3: HR 0.85, 95% CI: 0.54, 1.34, P=0.850; Q4: HR 1.13, 95% CI: 0.73, 1.76, P=1.13; Men:; Q2: HR 0.61, 95% CI: 0.33, 1.12, P=0.1136; Q3: HR 0.70, 95% CI: 0.36, 1.37, P=0.2968; Q4: HR 1.06, 95% CI: 0.56, 2.01, P=0.8526; Women; Q2: HR 0.83, 95% CI: 0.33, 2.09, P=0.6895; Q3: HR 1.12, 95% CI: 0.51, 2.46, P=0.7837; Q4: HR 1.22, 95% CI: 0.54, 2.76, P=0.6399; Summary: Null: HEI-C & T2D | - Did not account for: Family history of Diabetes; Other: Total E; - Diet assessment: 24-h recall once at baseline; - Outcomes: Ontario Diabetes Database; - Sensitivity analysis by including underweight individuals or excluding individuals with missing data did not change results. Results for each group after excluding T2D diagnosed in first 2 years of follow up: Q1: HR 1, ref; Q2: HR 0.71, 95% CI: 0.52,0.96; Q3: HR 0.82, 95% CI: 0.62, 1.10; Q4: HR 1.16, 95% CI: 0.87, 1.53.; - Limitations included 24-h assessed only once at baseline (distant; Effect of change cannot be investigated; current dietary score may not reflect contemporary guidelines; Food components are reported in relation to energy consumption.; - Funding: Project Initiation Fund via Public Health Ontario
Tertsunen, 2021^118^; Finland; Kuopio Ischaemic Heart Disease Risk Factor Study (KIHD); Analytic N=2332 T2D; 2285 FPG, FBI; Participant characteristics:; - Health: BMI, kg/m2: 26.5-26.7; - Leisure-PA, kcal/d: 108-170; - Alcohol intake: 49-95; - Meds for HTN: 17-26%; - Meds for Lipids: 0-1.3%; - Current smoker: 19-48%; - Family history of diabetes: 24-30%; - Family history CVD: 80-84%; - Race and/or Ethnicity: NR (Finnish); - SEP: Income, euros: 11,441-14,586; - Education, years: 8-9y; - Marital status, married: 80-91%; - Selection data: Eligible were men who were 42, 48, 54 or 60 y; Excluded participants with T2D at baseline, impaired fasting glucose or unknown diabetes at baseline, or with missing dietary intake data | Age at Dietary Pattern: 53y, mean (42 to 60 y at baseline); [underlined: Baltic Sea Diet Score modified (mBSD)]; [underlined: [modified Kanerva, 2014],] Positive: Vegetables (including legumes, roots); Fruits (all plus berries; Cereals (whole grains); Fish (Salmon; Freshwater); Low-fat Milk; PUFA/SFA & Trans FA; Negative: Red/Processed Meat; Total Fat; Neutral: Total alcohol; Methods: Index/Score | Follow-up: 19.3 y mean, T2D; [underlined: Risk of T2D]:Q4, HR: 1, ref; Q1, HR: 1.35, 95% CI: 1.03, 1.76; Q2, HR: 1.21, 95% CI: 0.90, 1.63; Q3, HR: 1.15, 95% CI: 0.88, 1.51; P-trend<0.028; Per 1-pt decrease, HR: 1.03, 95% CI: 1.005, 1.055; [underlined: Glucose]:; Q1, β: 4.56, 95% CI: 4.53, 4.59; Q2, β: 4.51, 95% CI: 4.47, 4.55; Q3, β: 4.51, 95% CI: 4.48, 4.55; Q4, β: 4.49, 95% IC: 4.46, 4.52; P trend=0.003; Per 1-pt decrease, β: 0.007, 95% CI: 0.003,0.011; [underlined: Insulin]: FBI,; Q1, β: 11.14, 95% CI: 10.73, 11.56; Q2, β: 10.91, 95% CI: 10.41, 11.41; Q3, β: 10.79, 95% CI: 10.37, 11.22; Q4, β: 10.53, 95% IC: 10.10, 10.96; P trend=0.049; Per unit decrease, β: 0.053, 95% CI: 0.005,0.112; Summary: Inverse: Baltic Sea Diet Score & T2D risk, FBG, insulin | - Did not account for: Race and/or ethnicity,; - Diet assessment: Food record (4d), once at baseline; - Outcomes: Combination of self-report and exam or discharge registry or reimbursement of medicine expenses; - Baltic Sea Diet Score adapted from the validated version due to “lack of information on vertain food items in our database,” the version used in this study not validated; - Funding: University of Eastern Finland (UEF) including Kuopio University Hospital; Juho Vainio Foundation to H-M Tertsunen
Teymoori, 2021^119^; Iran; Tehran Lipid and Glucose Study (TLGS); Analytic N=4624; Participant characteristics:; - Health: In those w/ T2D vs. w/o:; - HTN, 32.5% vs. 13.6%; p< 0.001; - FBG, mean mg/dl: 101.9 vs. 92.0; p< 0.001; - Race and/or Ethnicity: NR (Iranian); - SEP: Education graduated w/ vs. w/o T2D: 19.8% vs. 30.2%; p< 0.001; - Employed w/ vs. w/o T2D: 82.7% vs. 84.1%; p=0.411; Selection data: Excluded those on diabetes-control diet, lactating, pregnant, or with extreme energy intakes, diabetes, history of Ml, cerebral vascular accident, cancer, BMI < 18.5 or>40; missing smoking data | Age at Dietary Pattern: 40.8y, mean (>20 y); [underlined: Dietary Inflammation Score (DIS) [Byrd, 2019],] Positive (Anti-inflammatory): Vegetables (leafy greens and cruciferous), Tomatoes; Fruits (apples and berries); Vegetable and Fruits (deep yellow or orange); Fruits (other) and real fruit juices; Vegetables (other); Legumes; Fish; Poultry; Dairy (high-fat). Pro-inflammatory: red and organ meats, processed meats, added sugars; [underlined: Empirical dietary inflammatory pattern (EDIP) [Tabuna, 2016],] Positive (Anti-Inflammatory): Vegetables (dark yellow: carrots, or squash), Vegetables, leafy green (cabbage, spinach, or lettuce); Fruit juice (apple juice, cantaloupe juice, orange juice, or other fruit juice); Pizza; Snacks (cracker, or potato chips); Tea; Coffee. Negative (Pro-Inflammatory): Processed meat (sausage); Red meat (beef, or lamb); Organ meat (beef, calf, or chicken liver), Fish, canned tuna; Vegtables, other: mixed, green pepper, cooked mushroom, eggplant, zucchini, or cucumber); Refined grains (white bread, biscuit, white rice, pasta, or vermicelli); High- and low-energy beverages (cola with sugar, carbonated beverages with sugar, fruit punch drinks); Tomatoes; Methods: Index/Score | Follow-up: 5.71 y (mean); [underlined: Risk of T2D]:; EDIP; Q2, HR: 1.40, 95% CI: 1.01, 1.93; Q3, HR: 1.32, 95% CI: 0.86, 1.72; Q4, HR: 1.52, 95% CI: 1.08, 2.14; p-trend=0.038; DIS; Q2, HR: 0.85, 95% CI: 0.72, 1.31; Q3, HR: 0.89, 95% CI: 0.71, 1.34; Q4, HR: 0.36, 95% CI: 0.61, 1.20; p-trend=0.418; Summary: Null: DIS & T2D; Positive: EDIP & T2D | - Did not account for: Race/Ethnicity (Iranian), Alcohol (not consumed), Family history of diabetes; - Diet assessment: FFQ once (baseline); - Outcomes: Fasted blood samples and 2h OGTT collected; T2D based on ADA: FPG ≥ 126 mg/dl or 2-h post 75-g glucose load ≥ 200 mg/dl or use of anti-diabetes meds; - Alcohol not controlled for, although “due to religious and legal restrictions in the Iranian population, alcohol is not consumed, or its consumption is not reported”; - Funding: Shahid Beheshti University of Medical Sciences
Teymoori, 2023^120^; Iran; Tehran Lipid and Glucose Study (TLGS); Analytic N=1884, T2D; 1057 IR; Participant characteristics:; - Health: mean BMI 26.8 [4.9]; - T2D:3%; HTN 14%; MetS 17%; - Race and/or Ethnicity: NR (Iranian); - SEP: Education: ~24% diploma+; - Employed : ~80% employed; Selection data: Excluded those lactating, pregnant, or with extreme energy intakes, diabetes, history of Ml, stroke, cancer, 18y or younger, missing data (age, sex, IR, diabetes) | Age at Dietary Pattern: 39.9y, mean (>20 y); [underlined: Dietarv Insulin Resistance diet Score (DIR) [Tevmoori, 2023],] Positive: pickles, refned grains, doogh, lemon juice, sweetened beverages, fsh; Negative: starchy vegetables, snacks, low-fat dairy, broth, red meat, and high-fat dairy; Methods: Index/Score | Follow-up: ~3y (total); [underlined: Risk of T2D:] T1, HR: 1 ref; T2, HR: 2.34, 95% CI: 1.22, 4.47; T3, HR: 1.95, 95% CI: 1.02, 3.74; p-trend=0.058; [underlined: Insulin]: T1. HR: 1 ref; T2, HR: 1.34, 95% Cl: 0.81, 2.21; T3, HR: 1.65, 95% Cl: 1.01, 2.69; p-trend=0.047; [underlined: HOMA-IR:] T1,HR: 1 ref; T2, HR: 1.34, 95% Cl: 0.81, 2.21; T3, HR: 1.65, 95% Cl: 1.01, 2.69; p-trend=0.047; Summary: Positive: DIR & T2D and IR | - Did not account for: Race/Ethnicity (Iranian), Alcohol (not consumed), family history of diabetes; - Diet assessment: FFQ once (3rd survey); - Outcomes: Fasted (12-14h) blood samples and 2-h OGTT collected; T2D by ADA: FPG > 126 mg/dl or 2-h post 75-g glucose load ≥ 200 mg/dl or use of oral anti-diabetes meds; - Notably large CIs (close/including null); - Funding: Shahid Beheshti University of Medical Sciences
Tison, 2022^121^; USA; REGARDS; Analytic N=8750; Participant characteristics:; - Health: 41% elevated WC; 28% not PA; 49% never smoker; Those with T2D more likely to be Black, lower education, lower income, live in stroke buckle, current smoker, no/heavy alcohol use, elevated WC; - Race and/or Ethnicity: 27% Black; 73% White (‘biracial sample’); - SEP: Income, $/y: 10% <$20K; 21% $20-30K; 35% $35-74K; 24% $75K+; - Education: 5% < HS, 23% HS, 26% Some college, 46% college grad +; Selection data: Excluded those with baseline diabetes or missing data (diet; baseline diabetes) | Age at Dietary Pattern: 63.2y, mean; [underlined: Mediterranean Diet Score (MDS) [Trichopolou 2003]], Positive: Vegetables; Legumes; Fruit, Nuts; Cereals; Fish; MUFA/SFA. Negative: Red and Processed Meat; Dairy Products. Neutral: Alcohol; [underlined: DASH diet score [Funq, 2008]] Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Sodium; [underlined: Mediterranean-DASH Intervention for Neurocoqnitive Delav score [Morris 2015]], Positive: Green leafv vegetables; Vegetables; Beans; Berries; Nuts; Whole Grains; Seafood; Poultry; Olive oil; Wine. Negative: Red Meat; Cheese; Pastries and sweets; Butter and stick margarine; Fried/fast food; [underlined: ‘Plant-based’ [Judd, 2013]]: characterized by vegetables, fruits, beans, poultry, fish; [underlined: ‘Southern’ [Judd 2013]]: characterized by fried foods, organ meats, processed meats, eggs and egg dishes, added fats, high-fat dairy foods, SSBs, and bread; Methods: Index/Score and Factor or cluster analysis | Follow-up: ~10y; [underlined: Risk of T2D]: MDS; Q4, HR: 0.85, 95% CI: 0.68, 1.07; Q3, HR: 0.90, 95% CI: 0.72, 1.11; Q2, HR: 0.89, 95% CI: 0.71, 1.10; Q1, HR: 0.87, 95% Cl: 0.71, 1.07; p-trend=0.35; DASH; Q4, HR: 0.94, 95% Cl: 0.74, 1.18; Q3, HR: 1.09, 95% Cl: 0.89, 1.32; Q2, HR: 1.08, 95% Cl: 0.88, 1.31; Q1, HR: 1.11, 95% Cl: 0.91, 1.36; p-trend=0.23; MIND; Q4, HR: 1.16, 95% Cl: 0.92, 1.47; Q3, HR: 1.08, 95% Cl: 0.86, 1.34; Q2, HR: 1.20, 95% Cl: 0.98, 1.47; Q1, HR: 1.18, 95% Cl: 0.95, 1.46; p-trend=0.26; “Plant-based” DP; Q4, HR: 1.12, 95% Cl: 0.93, 1.35; Q3, HR: 0.94, 95% Cl: 0.77, 1.14; Q2, HR: 0.90, 95% Cl: 0.74, 1.10; Q1, HR: 0.91, 95% Cl: 0.75, 1.11; p-trend=0.06 “Southern” DP; Q4, HR: 1.27, 95% Cl: 1.02, 1.59; Q3, HR: 1.37, 95% Cl: 1.11, 1.70; Q2, HR: 1.42, 95% Cl: 1.15, 1.75; Q1, HR: 1.66, 95% Cl: 1.35, 2.06; p-trend=0.003; Summary: NS/Inverse: MDS & T2D; NS/Nuli: DASH & T2D; NS/Positive: MIND & T2D; NS/Inverse: ‘Plant-based’ DP & T2D; Positive: ‘Southern’ DP & T2D | - Did not account for: family history of diabetes; Anthropometry (WC differed at baseline and was not adjusted); - Diet assessment: FFQ once; - Outcomes: Fasted blood samples collected; T2D based on FPG ≥ 70 mmol/L, NFG ≥ 111 mmol/L, or reported use of anti-diabetes meds; - Funding: National Institute of Neurological Disorders and Stroke (NINDS) and the National Institute on Aging (NIA), NIH
Ushula, 2022^122^; Australia; Mater-University of Queensland Study of Pregnancy (MUSP); Analytic N=1103; Participant characteristics:; - Health: 13% Ob (BMI 30+); 21% OW (BMI 25-30); 67% NW (BMI <25); - Race and/or Ethnicity: NR (Australian birth cohort); - SEP: Income: 33% “high”, 44% “middle”; “low” 23%; Education: ~88% post-secondary or secondary;; Selection data: Excluded those with missing data (>40% on FFQ; outcomes) or implausible energy intake | Age at Dietary Pattern: ~21 y, mean; [underlined: ‘Western’]: high loadings for meats, fried and processed foods, and high-fat dairy products, low in whole grains and low-fat dairy products.; [underlined: ‘Prudent’]: hiqh loadings for vegetables, fruit, cereals and grains, nuts low-fat dairy products, and non-fat spreads, low in refined grains; Methods: Factor or cluster analysis | Follow-up: ~9y (mean age ~ 30y); [underlined: Prediabetes]: T1, RR: 1 ref; ‘Western’; T2, RR: 1.14, 95% CI: 0.59, 2.22; T3, RR: 0.96, 95% CI: 0.43, 2.14; p-trend=0.8681; ‘Prudent’; T2, RR: 0.63, 95% CI: 0.32, 1.26; T3, RR: 1.05, 95% CI: 0.51, 2.17; p-trend=0.8788; [underlined: Glucose]:; ‘Western’ & FPG; T2, 0.02, 95%CI:-0.08, 0.13; T3,-0.04, 95%CI:-0.16, 0.09; p-trend=0.5623; ‘Prudent’ & FPG; T2,-0.07, 95%CI:-0.16, 0.03; T3, 0.00, 95%CI:-0.11, 0.11; p-trend=0.9194; [underlined: Insulin]:; ‘Western’ & IS; T2, RR: 0.66, 95% CI: 0.50, 0.88; T3, RR:0.57, 95% CI: 0.39, 0.84; p-trend=0.0037; [underlined: ‘Prudent’ & IS]; T2, RR: 1.34, 95% CI: 0.98, 1.83; T3, RR: 1.84, 95% CI: 1.30, 2.60; p-trend=0.0005; [underlined: HOMA-IR]:; ‘Western’ & IR; T2, RR: 1.31, 95% CI: 0.91, 1.89; T3, RR:1.69, 95% CI: 1.07, 2.65; p-trend=0.0237; ‘Prudent’ & IR; T2, RR: 0.64, 95% CI: 0.91, 0.88; T3, RR: 0.57, 95% CI: 0.39, 0.82; p-trend=0.0031; Summary: Inverse: ‘Prudent’ (T3 v. T1) & Insulin Resistance; ‘Western’ (T3 v. T1) & Insulin Sensitivity Positive: ‘Western’ (T3 v. T1) & Insulin Resistance; ‘Prudent’ (T3 v. T1) & Insulin Sensitivity; NS/Null: Either ‘Prudent’ or ‘Western’ & Prediabetes | - Did not account for: Race/Ethnicity (Australian birth cohort); - Diet assessment: FFQ once (baseline); - Outcomes: Fasted (9h) blood samples collected; Insulin (Cation exchange-HPLC); HbA1C (Abbott Architect Immunochemistry with ICMA-calibrated to WHO 1st lRP method); - Funding: National Health and Medical Research Council, Australia
Vinke, 2020^123^; Netherlands; Lifelines cohort; Analytic N=91025; Participant characteristics:; - Health: BMI, kg/m2, male: 26.5 ± 3.4, female: 25.9 ± 4.5; Body weight, kg, Male: 88.3 ± 12.7, Female: 74.2 ± 13.4; - Glucose, mmol/l: 4.9 ± 0.5; - HbA1c, %: 5.5 ±0.3; - T2D incidence, total: 3.73% (male: 4.41%; female: 3.25%); - Smoking status, Current: 18.8%; - Non-occupational MVPA, min/wk: 180 [60-360]; - Alcohol-users: 83% (intake in g/d: 6.4 [2.5-12.4]); - Race and/or Ethnicity: 98.8% White/East & West European ethnicity; - SEP: Education: Low 30.91%; Middle: 38.38%; High (e.g. university): 30.71%; Selection data: Excluded participants without F/U data, under the age of 30y, with CVD or diabetes at baseline; pregnancy at baseline or F/U; missing or unreliable data on diet quality or covariates | DP Age(s):48y [10], mean (≥ 30 y); [underlined: Lifelines Diet score (LLDS) [Vinke, 2018],] Positive: Vegetables; Fruit; Legumes and Nuts; Whole Grains; Fish; Oils and Soft Margarines; Unsweetened Dairy; Tea; Coffee; Negative: Red and processed meats; Sugar-sweetened beverages; Butter and Hard Margarines; Methods: Index/Score | Follow-up: T2= 13 [12-14] mos; T3= 24 [23-27] mos; T4= 44 [35-51] mos; up to 60 mos; [underlined: Risk of T2D:] Q5, HR: 1,ref; Q1, HR: 1.87, 95% CI: 1.50, 2.31; Q2, HR: 1.40, 95% CI: 1.15, 1.71; Q3, HR: 1.19, 95% CI: 0.96, 1.46; Q4, HR: 1.15, 95% CI: 0.95, 1.40; p-trend <0.001; Summary: Inverse: LLDS & T2D | - Did not account for: Race and/or ethnicity, family history of diabetes; - Diet assessment: FFQ once; - Outcomes: T2D from combination of self-report of diagnosis since last visit or measured FPG ≥ 7 mmol/L, HbA1C ≥ 6.5% Fasted blood samples at T4; - Identified n=1045 cases; Stratified analysis by education: Low Education: Q1: HR 1.48, 95% CI: 1.09, 2.02; Q2: HR 1.25, 95% CI: 0.94, 1.67; Q3: HR 0.98, 95% CI: 0.72, 1.32; Q4: HR 1.01, 95% CI: 0.76, 1.33, P=0.028; Middle Edu: Q1: HR 2.55, 95% CI: 1.73,3.77; Q2:HR1.60, 95% CI: 1.09, 2.34; Q3: HR 1.42, 95% CI: 0.96, 2.09; Q4: HR 1.72,95% CI: 1.20,2.47, PO.001; High Edu: Q1 : HR 2.04, 95% CI: 1.26, 3.30; Q2: HR 1.56, 95% CI: 1.01, 2.41; Q3: HR 1.44, 95% CI: 0.93, 2.22; Q4: HR 0.88, 95% CI: 0.56, 1.36, P=0.003;; - Funding: none
Voortman, 2017^124^; Netherlands; Rotterdam Study; Analytic N=6772; Participant characteristics:; - Health: All free of T2D at baseline; Smoking status: 32.1% Never, 44.2% Ever, 23.8% Current; - Race and/or Ethnicity: NR; - SEP: Education Level: 16% Primary, 41% Lower, 28% Intermediate, 16% Higher; - 28% Paid Employment; Selection data: Excluded those with T2D at baseline; without reliable dietary data at baseline; missing incident T2D data | Age at Dietary Pattern: 64.1y, mean (≥45 y at baseline); [underlined: Dutch Dietary Guidelines - 2015 [Voortman 2017],] Positive: Veqetables; Legumes; Fruit; Nuts; Whole Grains; Fish; Dairy Products; Unsaturated Fats and Oils; Tea. Negative: Replace Refined with Whole-Grain Products; Red Meat; Processed Meat; Alcohol; Sodium; Methods: Index/Score | Follow-up: 7.3 y (median), up to 14.7y; [underlined: Risk of T2D]: HR: 1.03, 95% CI: 0.98, 1.07; Summary: NS/Null: Dutch Dietary Guidelines & T2D | - Did not account for: Race/Ethnicity,; - Family history of Diabetes; - Diet assessment: FFQ once (baseline); slightly different approach between cohorts (cohort included as covariate); index scoring not previously validated; - Outcomes: Combination of self-report (of diagnosis or meds) or pharmacy records; - No fasting blood samples collected in the first two visits of RS-I, so third visit (1997-1999) of RS-I set as baseline --> smaller sample size for T2D incidence; - Funding: Erasmus University Medical Center and Erasmus University Rotterdam; the Netherlands Organization for Health Research and Development; the Research Institute for Diseases in the Elderly; the Netherlands Genomics Initiative; the Ministry of Education, Cultu
Walsh, 2021^125^; Australia; PATH Through Life Project; Analytic N=2818; Participant characteristics:; - Health: NR; - Race and/or Ethnicity: NR; - SEP: 14.7y, mean education (Young: 15; Mid-life: 14.8; Late-life: 14.3); Selection data: Excluded those with missing dietary or T2D status available; T2D at baseline; missing data on multiple confounders | Age at Dietary Pattern: 46.3y, mean (20 to 65 y at baseline; mean 20-25y: 23.2; 40-45y: 43.2; 60-65y: 63); [underlined: ‘Western’], Positive: sausaqes, roast meat, chips and crisps, soft drinks, bread rolls, fried rice, pastaplus, cordial, popsicles, fried eggs, steak, pork, lamb, hamburgers, bacon, ham, schnitzel, moussaka, spicy mince, hamburger bun, pizza, meat pies, sauces & gravy, roast chicken fried chicken, coleslaw, potato salad, mayonaisse, mashed potato, roast potato, peas, frozen vegetables, chocolate bars, fat spreads (e.g., butter, margarine), bread; [underlined: ‘Prudent’,] Positive: fresh fruit (oranqe, apple, banana, berries, pineapple, avocado, fruit salad, melon, peach, plum, nectarine, apricot, grapes, dried apple), vegetables (carrots, zucchini, cabbage, brussel sprouts, spinach, broccoli, cauliflower, pumpkin, corn, tomato, lettuce, cucumber, celery, sprouts, capsicum), grilled fish, salad, water, yogurt, vegetable stew, canned fish, salad dressing, beans, vegetable stir fry, mushrooms, homemade soup, fresh nuts; Methods: Factor or cluster analysis: PCA | Follow-up: 12 y (mean); [underlined: Risk of T2D]:; [underlined: ‘Western’] & T2D, HR: 0.17, 95% CI: −0.10, 0.44; p-trend>0.05; [underlined: ‘Prudent’] & T2D, HR: −0.19, −0.41, 0.03;; p-trend>0.05; Summary: NS/Positive-Null: Western & T2D; NS/Inverse-Null: Prudent & T2D | - Did not account for: Race/Ethnicity, Alcohol, family history of diabetes; - Diet assessment: FFQ once (baseline); - Outcomes: Self-reported diagnosis or treated for T2D via diet or anti-diabetic agents; - Identified n=147 cases; Sample selection skewed towards older and female participants; - Funding: National Health and Medical Research Council
Wang F, 2022^126^; USA; HPFS/NHS I, NHS II; Analytic N=8827; Participant characteristics:; - Health: BMI, mean: 25.3 [4.7]; - Never smokers 52%; Family history of diabetes 29%; HTN: 20%; HC 27%; Meds for HTN, 16% or Lipids, 3%; - Race and/or Ethnicity: 96% White; - SEP: NR (all health professionals); Selection data: Excluded those with major chronic diseases at baseline (CVD, cancer, diabetes), LFU, or enrolled into the GDM sub-study | Age at Dietary Pattern: 54y [9]; [underlined: Plant-Based Diet Index (PDI) [Satiia, 2016]], Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Tea/coffee; Fruit juices; Veg. Oils; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Negative: Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; [underlined: Healthful PDI (hPDI) [Satiia, 2016]], Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Tea/coffee; Negative: Fruit juices; Veg. Oils; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; [underlined: unhealthful PDI (uPDI) [Satija, 2016],] Negative: Whole grains; Fruits; Vegetables; Nuts; Legumes; Tea/coffee; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; Positive: Fruit juices; Veg. Oils; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Methods: Index/Score | Follow-up: NR (~30y); [underlined: Risk of T2D]:; PDI, HR: 0.93, 95% CI: 0.85, 1.02 hPDI, HR: 0.93, 95% CI: 0.85, 1.01 uPDI, HR: 1.07, 95% CI: 0.98, 1.17; Summary: NS/lnverse: PDI & T2D; hPDI & T2D; NS/Positive: uPDI & T2D | - Did not account for: SEP (all health professionals); - Diet assessment: FFQ every 4y, validated; - Outcomes: Self-report confirmed with reported f/u based on NDDG criteria: classic symptoms and FPG ≥ 7.8 mmol/L (140 mg/dL; post-2010, 7 mmol/L) or NF ≥ 11.1 mmol/L (200 mg/dL); or no symptoms but 2+ elevated FBG or NF on different occasions or after OGTT; or Tx with anti-diabetes agents; or HbA1C ≥ 6.5% post-2010;; 729 cases identified; - Funding: NIH
Wang P, 2023^127^; USA; NHS, NHSII, HPFS; Analytic N=205,852; Participant characteristics:; - Health: F/U mean BMI~25; current smoking ~13-28%; - Race and/or Ethnicity: NR; - SEP: NR (all health professionals); Selection data: Excluded those with missing dietary data; implausible energy intake; baseline history of CVD, diabetes, Cancer (except non-melanoma skin cancer, non-fatal prostate cancer); extreme BMI (<15 or >50). Participants censored at 80y old | Age at Dietary Pattern: ~55y at f/u (mean); NHS: 30-55y; NHSII: 25-42y; HPFS: 40-75y; [underlined: Alternative HEI (AHEI)-2010] [Chiuve 2012], Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol; [underlined: Alternate Med Diet Score (aMED)] [Fung 2005], Positive: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA/SFA. Negative: Red and Processed Meat. Neutral: Alcohol; [underlined: Healthful PDI (hPDI)] [Satiia, 2016], Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Negative: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; [underlined: Diabetes Risk Reduction Diet (DRRD)] [Wang 2021], Positive: Whole Fruits; Nuts; PUFA:SFA ratio; Cereal fiber; Coffee. Negative: Red meat; Trans-fat; SSBs & fruit juices; Glycemic index (Gl); [underlined: DASH Score] [Funq 20081, Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Sodium; [underlined: WCRF/AICR Score − Diet Onlv [Shams-White 2019],] Positive: Vegetables; Fruit; Beans; Whole Grains. Negative: Red and Processed Meat; Sugary Drinks; Fast foods; Energy-Dense Foods; Neutral: Alcohol; [underlined: Empirical dietarv index for hvperinsulinemia (EDIH) [Tabunq, 2016],] Positive: Red meat; Processed meat; Poultry; Tomatoes; French fries, Fish (other than dark-meat fish); Low-fat dairy; Eggs; High-energy beverages (cola and other carbonated beverages with sugar, fruit drinks); Low-energy beverages; Margarine; Cream soups; Negative: Green leafy vegetables; Whole fruit; High-fat dairy products; Coffee; Wine; [underlined: Empirical dietarv inflammatory pattern (EDIP) [Tabung, 2016],] Anti-inflammatory group: tea, coffee, dark yellow vegetables (carrots, or squash), leafy green vegetables (cabbage, spinach, or lettuce), snacks (cracker, or potato chips), fruit juice (apple juice, cantaloupe juice, orange juice, or other fruit juice), pizza. Pro-inflammatory group: processed meat (sausage), red meat (beef, or lamb), organ meat (beef, calf, or chicken liver), other fish (canned tuna, or fish), other vegetable; Methods: Index/Score | Follow-up: 26y f/u (median); [underlined: Risk of T2D]:AHEI-2010; +SES, HR: 0.66, 95% CI: 0.63, 0.69; +BMI, HR: 0.73, 95% CI: 0.70, 0.77; aMED; +SES, HR: 0.74, 95% CI: 0.71, 0.77; +BMI, HR: 0.85, 95% CI: 0.82, 0.89; hPDI; +SES, HR: 0.71, 95% CI: 0.68, 0.73; +BMI, HR: 0.78, 95% CI: 0.75, 0.81; DASH; +SES, HR: 0.69, 95% CI: 0.66, 0.72; +BMI, HR: 0.77, 95% CI: 0.74, 0.81; DRRD; +SES, HR: 0.58, 95% CI: 0.56, 0.60; +BMI, HR: 0.66, 95% CI: 0.63, 0.69; WCRF/AICR; +SES, HR: 1.07, 95% CI: 1.02, 1.11; +BMI, HR: 0.95, 95% CI: 0.91, 0.99; EDIH (reverse coded, higher=healthier); +SES, HR: 0.36, 95% CI: 0.35, 0.37; +BMI, HR: 0.57, 95% CI: 0.54, 0.59; EDIP (reverse coded, higher=healthier); +SES, HR: 0.38, 95% Cl: 0.37, 0.40; +BMI, HR: 0.57, 95% Cl: 0.55, 0.59; Summary: Inverse: AHEI-2010, aMED, hPDI, DASH, DRRD, EDIH-reversed, EDIP-reversed & T2D NS/lnverse: WCRF/AICR (+BMI) & T2D (NS/Nuli: +SES or crude) | - Did not account for: Race/Ethnicity (sub-group analyses); - Diet assessment: FFQ every 4y; - Outcomes: Self-report, confirmed via NDDG <1988 or ADA >1988 criteria; subsample of cases confirmed by medical records; - No correction for multiple testing because authors “aimed to compare the patterns, some of which have been examined individually previously”; - Funding: NIH
Wang Y, 2022^128^; China; Guizhou Population Health Cohort Study (GPHCS; Analytic N=7203; Participant characteristics:; - Health: BMI 18.5-23.9, 64%; BMI 24-27.9: 25%, BMI 28+, 6%; - Current smoker 29%; Family history of diabetes, 1%; Alcohol use: 32%; - Race and/or Ethnicity: 58% Han Chinese; - SEP: Education: 42% 12y+; Married: 80%; Rural: 66%; Selection data: Included those 18y or older, with complete data, and no plan to move; Excluded those with missing 1+ FFQ item or had diabetes at baseline | Age at Dietary Pattern: 18 to 24y, 55%; 35 to 49y, 30%; 50y+, 16%; [underlined: ‘Junk food’]: hiqh factor loadings for fried food, soft drinks, and desserts; [underlined: ‘Veqetable-qrain’]: hiqh factor loadinqs for vegetables and grains; Methods: Factor or cluster analysis: PCA | Follow-up: 7.05y, mean; [underlined: Risk of T2D]:; ‘junk food’, Medium, HR: 1, ref; Low, HR: 0.72, 95% CI: 0.61, 0.87; High, HR: 0.93, 95% CI: 0.78, 1.11; ‘vegetable-grain’, Medium, HR: 1, ref; Low, HR: 0.86, 95% CI: 0.72, 1.02; High, HR: 0.80, 95% CI: 0.67, 0.95; Summary: Positive: “Junk food’ & T2D (low vs. medium only) Inverse: ‘Vegetable-grain’ & T2D (medium vs. high only) | - Did not account for: Family history of diabetes; - Diet assessment: FFQ once (unnknown if valid); - Outcomes: Fasted (8h+) blood samples and OGTT collected; T2D from self-report of diagnosis or anti-diabetes meds (confirmed via medical record); or FPG ≥ 7 mmol/L; OGTT or NFG ≥ 11.1 mmol/L); or HbAIC ≥ 6.5%; Impaired fasting glucose (IFG)6.01 up to 7 mmol/L; - 749 cases; - Funding: Guizhou Province Science and; - Technology Support Program
Xu, 2020^129^; USA; ARIC; Analytic N=10808; 7427 diet quality change; Participant characteristics:; - Health: Ob 27%; OW 38%; CVD, 16%; - Race and/or Ethnicity: NR; - SEP: SEIF, Low: 31%, Medium 34%, High 35%;; - Education, Low: 32%, Med. 42%, High 26%; - Marital status: Married/Partner 78%;Single/Divorced/Separated 14%; Widowed 7%; Selection data: Included participants aged 45 to 64 y who reported usual dietary intake via FFQ at visit 1. Excluded participants with CVD, diabetes, cancer at baseline, implausible/missing dietary intake, neither white nor African American; not from Minneapolis, Minnesota or Washington County, MD, missing covariates, and missing CVD or diabetes info prior to visit 3 or at visit 3 for diet quality change analysis | Age at Dietary Pattern: 45 to 64 y; [underlined: Healthy Eating Index (HEI-2015) [Krebs-Smith 2018],] Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; PUFA+MUFA/SFA. Negative: Refined Grains; Added Sugars; SFA; Sodium; [underlined: Alternative HEI ÍAHED-2010 [Chiuve 2012],] Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol; Methods: Index/Score | Follow-up: 6y; [underlined: Risk of T2D]:Q1, HR: 1, ref; HEI-2015; Q2: HR 1.00, 95% CI: 0.89, 1.11; Q3: HR 0.89, 95% CI: 0.79, 1.00; Q4: HR 0.93, 95% CI: 0.83, 1.05; Q5: HR 0.98, 95% CI: 0.87, 1.11; p-trend=0.433; AHEI-2010; Q2: HR 0.99, 95% CI: 0.88, 1.11; Q3: HR 0.98, 95% CI: 0.87, 1.10; Q4: HR 0.95, 95% CI: 0.84, 1.06; Q5: HR 0.96, 95% CI: 0.85, 1.08; P trend=0.347; Δ HEI-2015 (↓ decrease; ↑ increase),; Large ↓: HR 1.04, 95% CI: 0.88, 1.24; Small to Moderate ↓. HR 1.04, 95% CI: 0.89, 1.21; Small to Moderate ↑: HR 0.89, 95% CI: 0.77, 1.03; Large ↑: HR 0.99, 95% CI: 0.85, 1.14; Change in AHEI-2010; Large ↓: HR 1.12, 95% CI: 0.94, 1.35; Small to Moderate ↓: HR 1.11, 95% CI: 0.89, 1.37; Small to Moderate ↑: HR 1.01, 95% CI: 0.82, 1.25; Large ↑: HR 1.11, 95% CI: 0.93, 1.32; Summary: NS/Null: HEI-2015, AHEI-2010 at baseline or 6-y Δ & T2D | - Did not account for: N/A (all); - Diet assessment: FFQ at visits 1 and 3 (validated; change assessed); - Outcomes: Fasted blood samples collected; T2D based on FPG ≥ 126 mg/dL or NF/random ≥ 200 mg/dL, or self-reported diagnosis, or diabetes-meds; - Identified 3452 cases; Small sub-group size noted by authors; - Funding: NHLBI; NIH; NIDDK; China Scholarship Council
Xu, 2022^130^; United Kingdom; BIOBANK; Analytic N=59849; Participant characteristics:; - Health: mean BMI: 26.97; WC ~89 cm; Never smoker 58%; - Race and/or Ethnicity: 94% White; 2% Black or black background; 2% Chinese; <1% Asian or Asian British; <1% Mixed; 1% Other; - SEP: SES Quintiles: ~ 20% in each quintile from most to least deprived; - Education: 40% college/university; Selection data: Excluded those with <7 foods consumed in EAT-Lancet; implausible dietary intake; <1y F/U; with CVD, cancer, or diabetes at baseline | Age at Dietary Pattern: 56y, mean (40 to 69y); [underlined: EAT-Lancet Reference Diet [Valleio, 2022; EAT-Lancet Commission, 2019],] Positive: Whole grains & all grains, ≤ 464 g/d and whole grain fiber; Vegetables, ≥ 200 - ≤ 600 g/d; Fruits, ≥ 100 - ≤ 300 g/d; All nuts, ≥ 25 g/d. Negative: Dairy foods, ≤ 500 g/d; Beef and lamb, ≤ 14 g/d; Pork, ≤ 14 g/d; Chicken and other poultry, ≤ 58 g/d; Eggs, ≤ 25 g/d; Fish, ≤ 100 g/d; Dry beans, lentils & peas, ≤ 100 g/d; Soy foods, ≤ 50 g/d; Palm oil, ≤ 6.8 g/d; Lard or tallow, ≤ 5 g/d; Butter, 0 g/d; All sweeteners, ≤ 31 g/d. Neutral: Tubers or starchy vegetables, ≤ 100 g/d; Unsaturated oils, ≥ 20 - ≤ 80 g/d; Methods: Index/Score | Follow-up: 10y, median; [underlined: Risk of T2D]:; T2, HR: 0.90, 95% CI: 0.81, 1.01; T3, HR: 0.95, 95% CI: 0.81, 1.06; p-trend=0.249; per 1-pt, HR: 0.99, 95% CI: 0.96, 1.02; Summary: NS/lnverse: EAT-Lancet score & T2D | - Did not account for: Family history of diabetes; - Diet assessment: FFQ/24-h hybrid multiple times; - Outcomes: T2D from hospital records/linkage; - Identified 2461 cases; - Funding: National Natural Science Foundation of China; Scientific Research Foundation for Scholars of HZNU
Yu, 2022^131^; Netherlands; Maastricht Study; Analytic N=3441; Participant characteristics:; - Health: mean BMI 27.06 [4.5]; 17% history w CVD; mean FPG 6.04 [1.62] mmol/L; - Race and/or Ethnicity: 100% Caucasian (European ancestry); - SEP: Education: ~ 33% low, 27% mid, 38% high;; - HH Income: ~29% low, 40% mid, 22% high; Selection data: Exclued those without metabolic data, glucose metabolism data, incomplete or implausible dietary intake; non-Caucasian | Age at Dietary Pattern: 60y [8.21]; [underlined: Mediterranean Diet Score (MDS) [Trichopolou 2003],] Positive: Vegetables; Legumes; Fruit, Nuts; Cereals; Fish; MUFA/SFA. Negative: Red and Processed Meat; Dairy Products. Neutral: Alcohol; [underlined: DASH diet score [Funq, 2008],] Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Sodium; [underlined: Dutch Healthv Diet (DHD) based on Dutch Dietarv Guidelines 2015 [Looman, 2017 version],] Positive: Vegetables; Legumes; Fruit; Nuts; Whole Grains; Fish; Dairy Products; Tea. Negative: Fats and Oils; Red Meat; Processed Meat; Sweetened Beverages; Fruit juices; Alcohol; Salt/Sodium; Methods: Index/Score | Follow-up: 5.8y, mean (7y total); [underlined: Risk of T2D]:; Risk of either T2D or Prediabetes (“GMS”); MDS, T2, OR: 0.87, 95% CI: 0.73, 1.05; MDS, T3, OR: 0.59, 95% CI: 0.50, 0.70; MDS, p-trend=0.008; DASH, T2, OR: 0.77, 95% CI: 0.65, 0.92; DASH, T3, OR: 0.58, 95% CI: 0.48, 0.69; DASH, p-trend=0.001; DHD, T2, OR: 0.79, 95% CI: 0.63, 0.98; DHD, T3, OR: 0.69, 95% CI: 0.55, 0.87; DHD, p-trend<0.001; Risk of T2D in those w/ Prediabetes; MDS, T2, OR: 0.81, 95% CI: 0.62, 1.06; MDS, T3, OR: 0.60, 95% CI: 0.46, 0.78; MDS, p-trend=0.005; DASH, T2, OR: 0.93, 95% CI: 0.72, 1.20; DASH, T3, OR: 0.73, 95% CI: 0.56, 0.96; DASH, p-trend=0.037; DHD, T2, OR: 0.88, 95% CI: 0.68, 1.13; DHD, T3, OR: 0.64, 95% CI: 0.49, 0.83; DHD, p-trend=0.001; Risk of T2D in those w/ NGM; MDS, T2, OR: 0.98, 95% CI: 0.88, 1.18; MDS, T3, OR: 0.61, 95% CI: 0.49, 0.77; MDS, p-trend<0.001; DASH, T2, OR: 0.79, 95% CI: 0.63, 0.98; DASH, T3, OR: 0.69, 95% CI: 0.55, 0.87; DASH, p-trend<0.001; DHD, T2, OR: 0.85, 95% CI: 0.68, 1.06; DHD, T3, OR: 0.62, 95% CI: 0.48, 0.78; DHD, p-trend<0.001; [underlined: Prediabetes]: Risk in those w/ NGM; MED; T2, OR: 1.01, 95% CI: 0.78, 1.28; T3, OR: 0.79, 95% CI: 0.61, 0.97; p-trend=0.459; DASH; T2, OR: 0.79, 95% CI: 0.62, 1.00; T3, OR: 0.68, 95% CI: 0.53, 0.86; p-trend=0.036; DHD; T2, OR: 0.74, 95% CI: 0.58, 0.95; T3, OR: 0.59, 95% CI: 0.45, 0.73; p-trend=0.003; [underlined: HbA1C]:%; MDS, β: −0.716, 95% CI: −0.913, −0.519; p-trend<0.001; DASH, β: −0.191, 95% CI: −0.262, −0.121; p-trend<0.001; DHD, β: −0.098, 95% CI: −0.120, −0.076; p-trend<0.001; [underlined: HOMA-IR]:; MDS, β: −0.086, 95% CI: −0.111, −0.061; p-trend<0.001; DASH, β: −0.034, 95% CI: −0.043, −0.024; p-trend<0.001; DHD, β: −0.013, 95% CI: −0.016, −0.010; p-trend<0.001; Summary: Inverse: MDS & T2D & T2D, T2D/Prediabetes [NS/lnverse: MDS & Prediabetes only]; Inverse: DASH & T2D & T2D or Prediabetes; Inverse: DDG & T2D & T2D or Prediabetes | - Did not account for: Family history of diabetes; - Diet assessment: FFQ once; - Outcomes: Fasted (8h+) blood samples and OGTT collected for baseline metabolism status; Risk of T2D from normal glucose (NG) progression from prediabetes based on self-report; Risk categories based on: NGM, FPG <6.1 mmol/L; prediabetes, FPG 6.1-6.9 mmol/L and no anti-diabetes meds; T2D, FPG ≥7.0 mmol/L or hypoglycaemic meds; - Funding: European Regional Development Fund via OP-Zuid, the Province of Limburg, the Dutch Ministry of Economic Afairs; Stichting De Weijerhorst; the Pearl String Initiative Diabetes, the Cardiovascular Center; School for Cardiovascular Diseases; Care and Public Health Research Institute, School for Nutrition and Translational Research in Metabolism; Stichting Annadal; Health Foundation Limburg; grants from Janssen-Cilag B.V. and Novo Nordisk Farma B.V.
Zhang, 2023^132^; Sweden; Malmo Diet and Cancer (MDC) cohort; Analytic N=24494; Participant characteristics:; - Health: mean BMI 25.6; 61% HTN; 3% CVD; 6% cancer; 38% Never smokers; 6% non-consumers of alcohol; 53% high-PA; - Race and/or Ethnicity: NR (Swedish); - SEP: 15% university degree; Selection data: Excluded those with diabetes at baseline, missing legume info, missing covariates, non-European | Age at Dietary Pattern: 58.1y, mean; 44 to 74 y; [underlined: EAT-Lancet Reference Diet [Valleio, 2022; Stubbendorff, 2022; EAT-Lancet Commission, 2019], EAT-Lancet]: Positive: Whole grains & all grains; Vegetables; Fruits; All nuts. Negative: Dairy foods; Beef and lamb; Pork; Chicken and other poultry; Eggs; Fish; Dry beans, lentils & peas; Soy foods; Palm oil; Lard or tallow; Butter; All sweeteners. Neutral: Tubers or starchy vegetables; Unsaturated oils; Methods: Index/Score | Follow-up: 24.3y, median (14.8; 2.3; max: 29.7y); [underlined: Risk of T2D]:; 14-16, HR: 1.04, 95% CI: 0.93, 1.16; 17-19, HR: 0.90, 95% CI: 0.81, 1.01; 20-22, HR: 0.94, 95% CI: 0.83, 1.06; 23+, HR: 0.82, 95% CI: 0.70, 0.96; p-trend<0.01; Summary: Inverse: Highest EAT-Lancet scores & lower T2D risk | - Did not account for: Race/Ethnicity (Swedish); - Diet assessment: Diet history once (validated; interview + 7d menu + Q); - Outcomes: Combination of seven registries (90%) or exams (10%); T2D based on FBG ≥ 7 mmol/L and/or 2+ HbA1C ≥ 6%; Funding: Swedish Research Council, the Swedish Society for Medical Research, the Crafoord Foundation, the Albert Pahlsson Foundation, Medical Training and Research Agreement
Zhuang, 2021^133^; United Kingdom; BIOBANK; Analytic N=357,419; Participant characteristics:; - Health: 26-27.7, mean BMI; - Race and/or Ethnicity: 100% White of British decent; - SEP: Townsend Deprivation index −1.3+3.1; College: 26.1-39.7%; Income <18K euros 15.4-18.7%; 18K-30.9K 21.3-22.5; 31K-51.9K 23.6-24.2%; 52K-100K 18.7-20.8%; >100K 4.7-5.7; Selection data: Excluded if: CVD, cancer, T2D at baseline, Non-White, withdrawn consent, lack of genetic data, discordance between reported and geno-type inferred sex, incomplete data on diet. | Age at Dietary Pattern: 56 y, mean (40 to 69y); [underlined: Diet Qualitv Score]: Positive fruit, vegetables, whole grains, fish, dairy, vegetable oil. Negative: refined grains, processed meats, red meat, sugar-sweetened beverages; Methods: Index/Score | Follow-up: 8.1y, mean; [underlined: Risk of T2D]: β: −0.098 (0.015), p<0.001; HR: 0.91, 95% CI: 0.88, 0.93; [underlined: HbA1C]: β: −0.146 (0.007), p<0.001; Summary: Inverse: Diet Quality Score & T2D, HbA1C | - Did not account for: Family history of diabetes; TEI; - Diet assessment: FFQ once (baseline); - Outcomes: Self-report and hospital record; - Unclear if diet score was validated; Diet assessed once at baseline with a validated FFQ; 100% participants were of white british descent; - Funding: National Natural Science Foundation of China; China National Program for Support of Top-notch Young Professionals and China Postdoctoral Science Foundation

a Abbreviations: BMI, body mass index; DM, Diabetes; FBG, fasting blood glucose; FBI, fasting blood insulin; FFQ, Food frequency questionnaire; FPG, fasting plasma glucose; F/U, Follow-up HbA1C, Hemoglobin A1C; Homeostatic Model - Insulin Resistance HOMA-IR, ; HS, high school; HTN, hypertension; ITT, intent-to-treat; Med, Mediterranean; mo, month(s); N/A, Not applicable NR, not reported; NS, not statistically significant; Ob, Obesity; OW, Overweight; SEP/SES, Socioeconomic position/status; T2D, Type 2 Diabetes; TC, total cholesterol; TG, triglyceride; Tx, treatment; UPF, Ultra-processed food; WC, waist circumference; ∆, change; ♂ male; ♀ female

Table 13 Risk of bias for observational studies examining dietary patterns consumed by adults and older adults and risk of type 2 diabetes^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall
Ahmad, 2018^30^ | High | Low | Low | Low | Low | Some concerns | Some concerns | High
Ahmad, 2020^31^ | High | Low | Low | Low | Low | Low | Some concerns | High
Alae-Carew, 2020^32^ | High | Low | Some concerns | Low | Some concerns | High | Some concerns | High
Alhazmi, 2014^33^ | High | Low | Low | Low | Low | Low | Low | High
Allaire, 2020^34^ | Low | Low | Low | Some concerns | Low | Low | Some concerns | Some concerns
Andre, 2020^35^ | High | Some concerns | Low | Low | Low | Low | Low | Some concerns
Bantle, 2016^36^ | High | Some concerns | Some concerns | Low | Some concerns | Low | Low | High
Bao, 2016^37^ | High | Some concerns | Low | Low | Low | Some concerns | Some concerns | High
Beigrezaei, 2023^38^ | High | Low | Low | Low | Some concerns | High | High | High
Boonpor, 2022^39^ | High | Some concerns | Low | Low | Some concerns | Low | Some concerns | High
Brayner, 2021^40^ | Low | Low | Some concerns | Low | Some concerns | High | Some concerns | High
Cea-Soriano, 2021^41^ | High | Low | Low | Low | Low | Low | Low | High
Cespedes, 2016^42^ | Low | Low | Some concerns | Low | Some concerns | Low | Some concerns | Some concerns
Chen, 2018 Diet^43^ | High | Some concerns | Some concerns | Low | Low | Low | Some concerns | High
Chen, 2018 Plant^44^ | Some concerns | Some concerns | Some concerns | Low | Some concerns | Low | Some concerns | High
Chen, 2021^45^ | High | Low | Low | Low | Some concerns | Some Concerns | Low | High
Choi, 2020^46^ | High | Low | Low | Low | High | Low | Some concerns | High
Choi, 2023^47^ | High | High | Some concerns | Low | Low | Some concerns | Some concerns | High
Conway, 2018^48^ | High | Some concerns | Some concerns | Low | Some concerns | Some concerns | Low | High
den Braver, 2019^49^ | High | Some concerns | Low | Low | Low | Low | Low | High
Dominguez, 2015^50^ | High | Some concerns | Low | Low | Some concerns | Low | Some concerns | High
Dow, 2019^51^ | High | Low | Some concerns | Low | Some concerns | Low | Low | High
Duan 2022 Lifestyle^52^ | High | Low | Low | Low | High | Some concerns | Low | High
Duan, 2021^53^ | High | Some concerns | Low | Low | Some concerns | Some concerns | Some concerns | High
Duan, 2022^54^ | High | Some concerns | Low | Low | Some concerns | High | Some concerns | High
Eguaras, 2017^55^ | High | Low | Some concerns | Some concerns | Some concerns | Low | Some concerns | High
Ericson, 2018^56^ | High | Low | Low | Low | Low | High | Low | High
Ericson, 2019^57^ | Some concerns | Low | Some concerns | Low | Some concerns | Low | Some concerns | High
Esfandiar, 2022^58^ | High | Low | Low | Low | Low | Low | Some concerns | High
Farhadnejad, 2020^109^ | Some concerns | Some concerns | Low | Low | Some concerns | Low | Some concerns | High
Filippatos, 2016^60^ | Some concerns | Some concerns | Some concerns | Low | Some concerns | Low | Low | High
Freisling, 2020^61^ | High | Some concerns | Some concerns | Low | Some concerns | Some concerns | Some concerns | High
Fung, 2021^62^ | High | Low | Low | Low | Low | High | Low | High
Galbete, 2018^63^ | High | Some concerns | Low | Low | Low | Low | Some concerns | High
Gao, 2022^64^ | Low | Low | Low | Low | Some concerns | Some concerns | Some concerns | High
Glenn, 2023^65^ | Low | Some concerns | Low | Some concerns | Low | Some concerns | Some concerns | High
Glenn, 2021^66^ | Low | Low | Low | Some concerns | Low | Low | Some concerns | Some concerns
Hirahatake, 2019^67^ | Low | Low | Low | Low | Low | Low | Some concerns | Some concerns
Hlaing-Hlaing, 2022^68^ | High | Some Concerns | Some concerns | Low | Some concerns | High | Low | High
Hlaing-Hlaing, 2021^69^ | High | Some Concerns | Some concerns | Low | Some concerns | High | Low | High
Hodge, 2021^70^ | Some concerns | Some concerns | Low | Low | Some concerns | High | Some concerns | High
Howard, 2018^23^ | Some concerns | Some concerns | Some concerns | Low | Low | Some concerns | Some concerns | High
Jacobs, 2015^71^ | High | Some concerns | Some concerns | Low | low | some concerns | High | High
Jacobs, 2017 A priori^72^ | High | Some concerns | Some concerns | Low | Low | Some concerns | High | High
Jacobs, 2017 Dietary ^73^ | High | Some concerns | Low | Low | High | High | Some concerns | High
Jannasch, 2019^74^ | Low | Some concerns | Some concerns | Low | Some concerns | High | Low | High
Jin, 2021^75^ | Some concerns | Low | Some concerns | Low | Some concerns | Low | Low | High
Kanerva, 2014^76^ | Some concerns | Low | Some concerns | Low | Some concerns | Some concerns | Low | High
Kesse-Guyot, 2021^77^ | Very high | some concerns | Some concerns | Low | High | low | Some concerns | Very high
Khalili-Moghadam, 2019^78^ | Some concerns | Low | Some concerns | Low | Low | Low | Some concerns | Some concerns
Kim and Giovannucci, 2022^79^ | Low | Some concerns | low | Low | High | Some concerns | Some concerns | High
Koloverou, 2016 Adherence^80^ | Very high | Some concerns | low | Low | High | Some concerns | Some concerns | Very high
Koloverou, 2016 Dietary^81^ | High | Some concerns | Low | Low | High | High | Some concerns | High
Kroger/InterAct Consortium 2014^82^ | High | Some concerns | Some concerns | Low | Low | Some concerns | Low | High
Lacoppidan, 2015^83^ | High | Some concerns | Low | Low | Low | Some concerns | Some concerns | High
Langmann, 2023^84^ | High | Some concerns | Low | Low | Some concerns | High | Low | High
Laouali, 2021^85^ | Low | Some concerns | Low | Low | High | Some concerns | Some concerns | High
Lee, 2019 Diabetes^86^ | Low | Low | Low | Low | High | Some concerns | Low | High
Lee, 2019 Identification^87^ | Some concerns | Low | Some concerns | Low | Some concerns | Some concerns | Some concerns | High
Lee, 2020^88^ | Some concerns | Low | Some concerns | Low | Some concerns | Some concerns | Some concerns | High
Ley, 2016^89^ | Some concerns | Some concerns | Some concerns | Low | Low | Some concerns | Some concerns | High
Llavero-Valero, 2021^90^ | High | Some concerns | Some concerns | Low | low | Some concerns | low | High
Lopez, 2022^91^ | High | Low | Some concerns | Low | Low | low | High | High
Ma, 2022^92^ | High | low | Some concerns | Low | high | low | High | High
Maldonado, 2022^93^ | High | Low | Some concerns | Low | Some concerns | Low | Some concerns | High
Mandalazi, 2016^94^ | High | Some concerns | Some concerns | Low | Low | Some concerns | Some concerns | High
Markanti, 2021^95^ | Low | Low | Some concerns | Low | Some concerns | Low | Some concerns | Some concerns
Mattei, 2017^96^ | Some concerns | Low | Some concerns | Low | low | Some concerns | Some concerns | High
Merino, 2022^97^ | Low | Low | Low | Low | Some concerns | Low | Some concerns | Some concerns
Neuhouser, 2022^98^ | Low | Low | Some concerns | Low | Low | High | Some concerns | High
O’Connor, 2020^99^ | High | Low | Low | Low | Some concerns | Low | Low | High
Otto, 2015^100^ | Some concerns | High | Low | Low | Some concerns | High | Some concerns | High
Pant, 2024^101^ | Some concerns | High | Some concerns | Low | Some concerns | High | Some concerns | High
Papier, 2019^102^ | High | High | Some concerns | Low | Low | High | Low | High
Pastorino, 2016^103^ | High | Some concerns | low | Low | high | Some concerns | low | High
Qiao, 2014^104^ | Low | Some concerns | Low | Low | Low | Some concerns | Low | Some concerns
Rajaobelina, 2019^105^ | High | Some concerns | low | Low | Some concerns | Some concerns | Some concerns | High
Rayner, 2020 ^106^ | Some concerns | Some concerns | Low | Low | Some concerns | Some concerns | Low | High
Riboldi, 2022^107^ | Low | Low | High | Low | High | Low | Some concerns | High
Ruiz-Estigarribia, 2020^108^ | High | Some concerns | Low | Low | Some concerns | High | Low | High
Sali, 2020^109^ | Some concerns | Some concerns | Low | Low | Some concerns | Low | Some concerns | High
Satija, 2016^110^ | Low | Low | Low | Low | Some concerns | Some concerns | Some concerns | Some concerns
Seah, 2019^111^ | High | Some concerns | Low | Low | Some concerns | Some concerns | Low | High
Shah, 2021^112^ | Some concerns | Some concerns | Low | Low | Low | Some concerns | Low | Some concerns
Shan, 2018^113^ | Some concerns | Low | Some concerns | Low | Some concerns | Some concerns | Low | High
Song, 2018^114^ | Some concerns | Some concerns | Some concerns | Low | Some concerns | Low | Low | High
Song, 2021^115^ | High | High | Some concerns | Low | High | Some concerns | Some concerns | High
Srour, 2020^116^ | Some concerns | Some concerns | Low | Low | Some concerns | Some concerns | Low | High
Tait, 2020^117^ | High | Some concerns | Some concerns | Low | Some concerns | Low | Low | High
Tertsunen, 2021^118^ | Some concerns | Some concerns | Low | Low | Low | Some concerns | Low | High
Teymoori, 2021^119^ | Some concerns | High | Low | low | Low | Low | Some concerns | High
Teymoori, 2023^120^ | High | Some concerns | Low | Low | Some concerns | Low | Some concerns | High
Tison, 2022^121^ | High | Some concerns | Some concerns | Low | Low | Low | High | High
Ushula, 2022^122^ | High | Low | Low | Low | High | Low | Low | High
Vinke, 2020^123^ | Some concerns | Low | Some concerns | Low | Some concerns | High | Low | High
Voortman, 2017^124^ | High | Some concerns | Some concerns | Low | Some concerns | High | Some concerns | High
Walsh, 2021^125^ | High | High | low | low | Some concerns | Some concerns | low | High
Wang, 2022^126^ | Some concerns | Low | Some concerns | Low | low | Some concerns | Some concerns | High
Wang, 2023^127^ | high | some concerns | low | low | Some concerns | low | Some concerns | High
Wang, 2022^128^ | High | Some concerns | Low | Low | Low | low | low | High
Xu, 2020^129^ | High | Some concerns | Low | Low | Some concerns | High | Some concerns | High
Xu, 2022^130^ | High | Low | Some concerns | Low | low | Some concerns | Some concerns | High
Yu, 2022^131^ | High | Low | Low | Low | Low | High | low | High
Zhang, 2023^132^ | Some concerns | Some concerns | Low | Low | Low | Low | Some concerns | High
Zhuang, 2021^133^ | high | Some concerns | Low | low | Some concerns | Some concerns | low | High

a Possible ratings of low, some concerns, high, very high, not applicable, or no information were determined using the “Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)” tool ( ROBINS-E Development Group, Higgins J, Morgan R, Rooney A . Risk Of Bias In Non-randomized Studies - of Exposure (ROBINS-E). Launch version, 1 June 2022. Available from: https://www.riskofbias.info/welcome/robins-e-tool. )