# Introduction

To prepare for the development of the Dietary Guidelines for Americans, 2025-2030, the U.S. Departments of Health and Human Services (HHS) (Appendix 1: Abbreviations) and Agriculture (USDA) identified a proposed list of scientific questions based on relevance, importance, potential federal impact, and avoiding duplication, which were posted for public comment.^*^ The Departments appointed the 2025 Dietary Guidelines Advisory Committee (Committee) in January 2023 to review evidence on the scientific questions. The Committee’s review of the evidence forms the basis of the Scientific Report of the 2025 Dietary Guidelines Advisory Committee^†^ which includes independent, science-based advice and recommendations to HHS and USDA and is considered as the Departments develop the next edition of the Dietary Guidelines.

* Dietary Guidelines for Americans: Learn About the Process. 2022. Available at: https://www.dietaryguidelines.gov/work-under-way/learn-about-process

† 2025 Dietary Guidelines Advisory Committee. 2024. Scientific Report of the 2025 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Health and Human Services and Secretary of Agriculture. U.S. Department of Health and Human Services. 10.52570/DGAC2025

The proposed scientific questions were refined and prioritized by the Committee for consideration in their review of the evidence. As part of that process, the following systematic review question was prioritized: What is the relationship between dietary patterns consumed and risk of type 2 diabetes?

The Committee conducted a systematic review to answer this question, with support from USDA’s Nutrition Evidence Systematic Review (NESR) team. This review is an update to systematic reviews conducted by the 2020 Dietary Guidelines Advisory Committee and the Dietary Patterns Systematic Reviews Project (Table 1). The conclusion statements developed as part of that existing work can be found in Appendix 2: Conclusion statements from the existing systematic reviews.

Table 1 Review history

Date | Description | Citation
August 2014 | Original systematic review conducted by the Dietary Patterns Technical Expert Collaborative published in 2014 | Dietary Patterns Technical Expert Collaborative and NESR Staff. A Series of Systematic Reviews on the Relationship Between Dietary Patterns and Health Outcomes. March 2014. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://nesr.usda.gov/sites/default/files/2019-06/DietaryPatternsReport-FullFinal2.pdf
July 2020 | Updated systematic review protocol applied by the 2020 Dietary Guidelines Advisory Committee published as an updated systematic review for children and adolescents, and as an evidence scan for adults and older adults | Boushey C, Ard J, Bazzano L, Heymsfield S, Mayer-Davis E, Sabaté J, Snetselaar L, Van Horn L, Schneeman B, English LK, Bates M, Callahan E, Butera G, Terry N, Obbagy J. Dietary Patterns and Risk of Type 2 Diabetes: A Systematic Review. July 2020. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.DGAC2020.SR0103
May 2023 | Systematic review protocol for the 2025 Dietary Guidelines Advisory Committee published online | Hoelscher DM, Anderson C, Booth S, Deierlein A, Fung T, Gardner C, Giovannucci E, Raynor H, Stanford FC, Talegawkar S, Taylor C, Tobias D, Obbagy J, Callahan EH, English LK, Fultz A, Raghavan R, Reigh N, Higgins M, Butera G, Terry N. Dietary Patterns and Risk of Type 2 Diabetes: A Systematic Review Protocol. May 2023. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://nesr.usda.gov/protocols
October 2023 | Revisions to the systematic review protocol for the 2025 Dietary Guidelines Advisory Committee published online | Hoelscher DM, Anderson C, Booth S, Deierlein A, Fung T, Gardner C, Giovannucci E, Raynor H, Stanford FC, Talegawkar S, Taylor C, Tobias D, Obbagy J, Callahan EH, English LK, Fultz A, Raghavan R, Reigh N, Higgins M, Butera G, Terry N. Dietary Patterns and Risk of Type 2 Diabetes: A Systematic Review Protocol. May 2023. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://nesr.usda.gov/protocols
June 2024 | Revisions to the systematic review protocol for the 2025 Dietary Guidelines Advisory Committee published online | Hoelscher DM, Anderson C, Booth S, Deierlein A, Fung T, Gardner C, Giovannucci E, Raynor H, Stanford FC, Talegawkar S, Taylor C, Tobias D, Obbagy J, Callahan EH, English LK, Fultz A, Raghavan R, Reigh N, Higgins M, Butera G, Terry N. Dietary Patterns and Risk of Type 2 Diabetes: A Systematic Review Protocol. May 2023. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://nesr.usda.gov/protocols