# Plain-language summary

### What is the question?

The question is: What is the relationship between dietary patterns consumed and risk of type 2 diabetes? The population of interest included infants and young children up to age 24 months, children and adolescents, and adults and older adults.

### Why was this question asked?

This systematic review was conducted by the 2025 Dietary Guidelines Advisory Committee as part of the process to develop the Dietary Guidelines for Americans, 2025-2030.

### How was this question answered?

The Committee conducted a systematic review to answer this question with support from the USDA Nutrition Evidence Systematic Review team. This review updated existing systematic reviews that were conducted by the 2020 Dietary Guidelines Advisory Committee and as part of the Dietary Patterns Systematic Reviews Project.

### What is the answer to the question?

#### Children and Adolescents

- A conclusion statement cannot be drawn about the relationship between dietary patterns consumed by children and adolescents and risk of type 2 diabetes because of substantial concerns with directness. (Grade Not Assignable)

#### Adults and Older Adults

- Dietary patterns consumed by adults and older adults that are characterized by higher intakes of vegetables, fruits, legumes, nuts, whole grains, and fish/seafood and lower intakes of red and processed meats, high-fat dairy products, refined grains, and sugar-sweetened foods and beverages are associated with lower risk of type 2 diabetes. This conclusion statement is based on evidence graded as strong.

### How up-to-date is this systematic review?

Conclusion statements from this review are based on articles published between January 1980 and May 2023.