# Appendix 6 Dietary pattern visualization

The Committee’s synthesis was facilitated by data visualization tables that presented the dietary pattern components in each of the dietary patterns examined in the body of evidence. During evidence synthesis, these tables were used in conjunction with other materials to compare and contrast the components between and within the dietary patterns studied along with the direction, magnitude, and statistical significance of reported results. Detailed information about the body of evidence, including study and population characteristics, a full description of each dietary pattern, reported results for all relevant outcomes, key confounders accounted for, study limitations, and funding sources, are summarized in the evidence tables of this report (Table 10; Table 12). Each column represents the most commonly reported foods/food groups or nutrients across dietary patterns in this body of evidence. Two additional columns, “Other, A” and “Other, B”, captured a variety of other components less frequently reported across dietary patterns that did not fit into one of the preceding columns or categories, such as fast food, ready-to-eat dishes, pizza, and chocolate. Multiple symbols in each cell mean that the dietary pattern included multiple components from that column/category. Empty cells mean that the dietary pattern did not describe a component within that column/category.

Table A 9 Visualization of dietary pattern components across dietary patterns consumed by adults and older adults from intervention studies organized alphabetically by first-author last name^*,,†^

Article; Dietary patterns compared | Vegetables | Potato | Legumes | Fruit | Fruit Juice | Nuts, Seeds | Grains: Whole | Grains | Grains: Refined | Fish | Seafood, shellfish | Meats (Red Processed) | Lean meats | Eggs | Dairy | Dairy: Low, non-fat | Dairy: Whole fat | Sugary Beverages | Sugary foods | Fat: Unsaturated, Oils | Fat: Other | Fat: Saturated | Alcohol | Sodium | Other, A | Other, B
Babio, 2014; Med+Evo v. Med+Nuts v. Control | ▲; ▲ | | ▲ | ▲ | Fr | ◄ | | ▲ | | ▲ | FS | ▼ RP | ▲ | ◄ | ▼ | ◄ ch | | | | ▲ evo | | | ◄ w | | ◄
Babio, 2014; Med+Evo v. Med+Nuts v. Control | ▲; ▲ | | ▲ | ▲ | Fr | ▲ | | ▲ | | ▲ | FS | ▼ RP | ▲ | ◄ | ▼ | ◄ ch | | | | ◄ evo | | | ◄ w | | ◄
Bruno, 2020; IG vs. Control | ▲; ▲ | | ▲ | ▲ | | ▲ | | | ▼ | ▲ | | ▼ RP | ▲ | | | | | ▼ | | ▲ oo; ▲ oo; to cook | | ▼ | ▲ rw
Calvo-Malvar, 2021 B; Atlantic v. Control | ▲ | ▲ | ▲ | ▲ | | ▲ | ▲ | ▲ | ▼ | ▲ | FS | ▼ | ▲ | ▲ | ▲ | | | | ▼ | ▲ oo | | ▼; ▼ | ◄ w | | ▲
Georgoulis, 2020; 2021, 2023; MDG v. SCG | ▲ | | ▲ | ▲ | | | ▲ | | | ▲ | FS | ▼R; ▼P | ▲ | | ▲ | | | ▼ | ▼ | ▲ oo | | | ◄ | ▼ salt
Gotfredsen, 2021; OFF v. HAB | | | | | | | | | | | | | | | | | | | | | | ▼
Gotfredsen, 2021; SUB v. HAB | ▲ | | | | | | ▲ | | | | | | | | | | | | | ▲ | | ▼ | | | ▲ | ▼ V
Howard, 2018; Low-fat v. Control | ▲ | | | ▲ | | | | ▲ | | | | | | | | | | | | | ▼ | ▼
Pavić, 2019; RCT: MD v. SHD | | | | | | ▲ | | | | ▲ | | | | | | | | | | ▲ oo
Reidlinger, 2015; DG v. Control | ▲ | | | ▲ | | | ▲ | | | ▲ | | ▼ | ▼ | | | | | ▼ | ▼ | | ▼ | ▼ | | ▼ salt
Sidahmed, 2014; Med v. ‘Healthy-eating’ arm | ▲ | | | ▲ | | | ▲ | | | | | | | | | | | | | ▲
Tussing-Humphreys, 2022; MedDiet v. Control | ▲ | ▲ | ▲ | ▲ | | L | ▲ | | | ▲ | | ▼ | ▼ | | | | ▼ | | | ▲ oo | | | ◄ ◄ w
Prentice, 2019; Low-fat v. Control | ▲ | | | ▲ | | | | ▲ | | | | | | | | ▲ | | | | | ▼
Salas-Salvado, 2014; Med+evo v. Control | ▲; ▲ | | ▲ | ▲ | Fr | ◄ | | ▲ | | ▲ | FS | ▼ RP | ▲ | ◄ | ▼ | ◄ ch | | | | ▲ evo | | | ◄ w | | ◄
Salas-Salvado, 2014; Med+Nuts v. Control | ▲; ▲ | | ▲ | ▲ | Fr | ▲ | | ▲ | | ▲ | FS | ▼ RP | ▲ | ◄ | ▼ | ◄ ch | | | | ◄ evo | | | ◄ w | | ◄

* ▲ Positively-scored component, reflecting higher intake within the food category as part of the pattern; ▼ Negatively-scored component, reflecting lower intake within the food category as part of the pattern; ◄ Neutral component, reflecting moderate (in contrast to higher or lower) intake within the food category as part of the pattern. Dietary approaches included this table are from a priori investigator-assigned intervention and/or index/score analysis as indicated. The dietary pattern labels are abbreviated in this table due to limited space, but full details about each dietary pattern are described in Table 10

† Abbreviations: ch, cheese; evo, extra-virgin olive oil; Fr, included with Fruits; FS, included with Fish or Seafood; L, included with Legumes; M, meat/ products; Med, Mediterranean; NP, not processed; NS, not sweetened; oo, olive oil; P, processed; RP, red and processed; rw, red wine; UP, ultra-processed; w, wine;

Table A 10 Visualization of dietary pattern components across dietary patterns consumed by adults and older adults from observational studies organized alphabetically by first-author last name^*,,†^

Article; Dietary pattern | Vegetables | Potato | Legumes | Fruit | Fruit Juice | Nuts, Seeds | Grains: Whole | Grains | Grains: Refined | Fish | Seafood, shellfish | Meats (Red Processed) | Lean meats (Poultry) | Eggs | Dairy | Dairy: Low, non-fat | Dairy: Whole, high fat | Sugary Beverages | Sugary Foods | Fat: Unsaturated, Oils | Fat: Other | Fat: Saturated | Alcohol | Salty food (Sodium Na^+^) | Tea and Coffee | Other A | Other B
Ahmad, 2018; a priori: tMED | ▲ | X | ▲ | ▲ | | Fr | | ▲ | | ▲ | | ▼ RP | | | ▼ | | | | | ▲ UF:SF | | UF: SF | ◄
Ahmad, 2020; a priori: mMDS | ▲ | | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼ RP | | | | | | | | ▲ UF:SF | | UF: SF | ◄
Alae-Carew, 2020; LCA: Stage 1’ | ▼ | ◄ | ◄ | ◄ | | | | | ◄ | | ▲ | ◄ R | ◄ | ▼ | | | | | | | | | | | | ▲ UP
Alae-Carew, 2020; LCA: Stage 2’ | ▼ | ▲ | | ▼ | | | | | ▼ | | | | ▼ | ▼ | ▼ | | | | | | | | | | | ▼ UP | ▲ V
Alae-Carew, 2020; LCA: Stage 3’ | ▼ | ▲ | ▼ | ▼ | | | ▼ | | ▼ | | | ▼ R | ▼ | ▼ | ▼ | | | | | | | | | | | ▼ UP | ◄ V
Alae-Carew, 2020; LCA: Stage 4’ | ▲ | | ◄ | ▲ | | | | | ◄ | | | ▲ R | ▲ | | ▲ | | | | | | | | | | | ▲ UP | ◄ V
Alhazmi, 2014; a priori: ARFS | ▲ | | ▲ pro | ▲ | | L, pro | | ▲ | | L, pro | | ▼ | ▼ | | | ▲ | | | | | ◄ | | ◄
Alhazmi, 2014; a priori: aDGI | ▲ | | ▲ | ▲ | | | ▲ | ▲ | | ▲ pro | | | F, pro | | ▲ | | | ▼ | SB | | ▼ | | ◄ | | | ▼
Allaire, 2020; a priori: aHEI2010 | ▲ | X | ▲ | ▲ | SB | LN | ▲ | | | | | ▼ RP | | | | | | ▼ | | ▲ ▲ | ▼ Tr | | ◄ | ▼ Na^+^
Andre, 2020; a priori: LitMDS | ▲ | | ▲ | ▲ | | Fr | | ▲ | | ▲ | | ▼ | | | ▼ | | | | | ▲ | | | ◄
Bantle, 2016; a priori: AmMDS | ▲ | ▼ | ▲ | ▲ | | Fr | ▲ | | ▼ | ▲ | FS | ▼ RP | | ▲ | ▼ | ▲ milk | milk | ▼ | | ▲ UF:SF | | UF: SF | ◄ | | | ▼
Bao, 2016; a priori: LCDs | ▼ | | | ▼ | | ◄ | ▼ | | | ◄ | | ▲ | ◄ | ◄ | | | | ▼
Beigrezaei, 2023; PCA: DP1 | | | | | ▲ | | ▼ | | | ▲ | | ▲ P | | | | | | ▲ | ▲ | | ▲ | | | | | ▲▲
Beigrezaei, 2023; PCA: DP2 | ▲ ▲ | ▲ | | ▲ | | | | | ▲ | | | | | | ▲ | | | | | ▲
Beigrezaei, 2023; PCA: DP3 | | | | | ▲ | | ▼ | | | ▲ | | ▲ P | | | | | | ▲ | ▲ | | ▲ | | | | | ▲▲
Beigrezaei, 2023; PLS: DP1 | | | | | ▼ | | ▲ | | | ▼ | | ▼ P | ▼ | | | | | | ▼ | | ▼ | | | | | ▼ ▼
Beigrezaei, 2023; PLS: DP2 | | ▼ | | | | | | | ▼ | | | | | | | | | | ▼ | ▼ | | | | | ▼ T
Beigrezaei, 2023; PLS: DP3 | ▲ ▲ | | | ▲ | | | | | | | | | | | ▲ | | | | | | ▼
Beigrezaei, 2023; RRR: DP1 | | | | | ▼ | | ▲ | | | ▼ | | ▼ RP | ▼ | | | | | ▼ | ▼ | | ▼ | | | | | ▼
Beigrezaei, 2023; RRR: DP2 | | ▼ | | ▲ | | | | | ▼ | | | | ▲ | | ▲ | | | ▲ | | | | | | | | ▼
Beigrezaei, 2023; RRR: DP3 | | | | ▲ | ▲ | | | | ▲ | | | ▼ | | | | | | | | ▲ | ▼ | | | | | ▼
Boonpor, 2022; Other: ‘Vegetarian’ | | | | | | | | | | X | | X | X | | ▲
Boonpor, 2022; Other: ‘Fish eater’ | | | | | | | | | | ▲ | | X | X | | ▲
Boonpor, 2022; Other: ‘Fish & poultry eater’ | | | | | | | | | | ▲ | | X | ▲ | | ▲
Boonpor, 2022; Other: ‘Meat eater’ | | | | | | | | | | ▲ | | ▲ R | ▲ | | ▲
Brayner, 2021; RRR: DP1 | | | | ▼ | | ▲ | | | | | | | | | | ▼ | | | | | | ▲
Brayner, 2021; RRR: DP2 | | | | | | ▼ | | | | | | | | | | | ▲ | | | | | ▲
Cea-Soriano, 2021; a priori: adMedDietScore | ▲ | ▲ | ▲ | ▲ | | ▲ | ▲ | ▲ | | ▲ | | ▼ ▼ | M | | | | | | ▼ | ▲ VO | | ▼ | ▼ | | | ▼ ▼ ▼
Cespedes, 2016; a priori: aMED | ▲ | X | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼ RP | | | | | | ▼ | | ▲ | | ▼ | ◄ | ▼ Na^+^
Cespedes, 2016; a priori: HEI-2010 | ▲ ▲ | V | V | ▲ ▲ | | | ▲ | | ▼ | ▲ pro | F, pro | F, pro | F, pro | | ▲ | | | ▼ | SB | ▲ | | ▼ | | ▼ Na^+^
Cespedes, 2016; a priori: aHEI-2010 | ▲ | X | ▲ | ▲ | SB | LN | ▲ | | | | | ▼ RP | | | | | | ▼ | | ▲ ▲ | ▼ Tr | | ◄ | ▼ Na^+^
Cespedes, 2016; a priori: DASH | ▲ | X | ▲ | ▲ | Fr | LN | ▲ | | | | | ▼ RP | | | | ▲ | | ▼ | | | | | | ▼ Na^+^
Chen, 2018_Am; a priori: aMED | ▲ | X | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼ RP | | | | | | ▼ | | ▲ | | ▼ | ◄ | ▼ Na^+^
Chen, 2018_Am; a priori: aHEI2010 | ▲ | X | ▲ | ▲ | SB | LN | ▲ | | | ▲ | | ▼ RP | | | | | | ▼ | | ▲ ▲ | ▼ Tr | | ◄ | ▼ Na^+^
Chen, 2018_Am; a priori: DASH | ▲ | X | ▲ | ▲ | Fr | LN | ▲ | | | | | ▼ RP | | | ▲ | ▲ | | ▼ | | | | | | ▼ Na^+^
Chen, 2018_Am; a priori: PDI | ▲ | ▲ | ▲ | ▲ | ▲ | ▲ | ▲ | | ▲ | ▼ | FS | ▼ | M | ▼ | ▼ | | | ▲ | ▲ | ▲ | | ▼ | | | ▲ | ▼ AP
Chen, 2018_Am; a priori: hPDI | ▲ | ▼ | ▲ | ▲ | ▼ SB | ▲ | ▲ | | ▼ | ▼ | FS | ▼ | M | ▼ | ▼ | | | ▼ | ▼ | ▲ | | ▼ | | | ▲ | ▼ AP
Chen, 2018_Eur; a priori: aPDI | ▲ | ▲ | ▲ | ▲ | ▲ | ▲ | ▲ | | ▲ | ▼ | FS | ▼ RP | ▼ | ▼ | ▼ | ▼ | ▼ | ▲ | ▲ | ▲ | | ▼ | ▲ | | ▲ | ▼ D; ch
Chen, 2021; a priori: PDI | ▲ | ▲ | ▲ | ▲ | ▲ | ▲ | ▲ | | ▲ | ▼ | FS | ▼ | M | ▼ | ▼ | | | ▲ | ▲ | ▲ | | ▼ | X | | ▲ | ▼ AP
Chen, 2021; a priori: hPDI | ▲ | ▼ | ▲ | ▲ | ▼ SB | ▲ | ▲ | | ▼ | ▼ | FS | ▼ | M | ▼ | ▼ | | | ▼ | ▼ | ▲ | | ▼ | | | ▲ | ▼ AP
Chen, 2021; a priori: uPDI | ▼ | ▲ | ▼ | ▼ | ▼ | ▼ | ▼ | | ▲ | ▼ | FS | ▼ | M | ▼ | ▼ | | | ▲ | ▲ | ▼ VO | | ▼ | | | ▼ | ▼ AP
Choi, 2020; a priori: aPDQS | ▲ | ◄ | ▲ | ▲ | ◄ | ▲ | ▲ | | ◄ | ▲ | ◄ | ▼ | ◄ | ◄ | | ▲ | ▼ | ▼ | ▼ | ▲ | ◄ | ▼ | ▲ | ▼ | ▲ | ◄ ◄ | ▼▼
Choi, 2023; a priori: aPDQS | ▲▲▲▲ | ◄ | ▲▲ | ▲ ▲ | ◄ | ▲ | ▲ | | ◄ | ▲ not fried | ◄ | ▼▼P▼ | ▲ | ◄ | | ▲ | ▼ | ▼ | ▼▼ | ▲ | ◄ | ▼ | ▲ | ▼ | ▲ | ◄ ◄ ◄ ◄ ◄ | ▼▼ ▼ ▼
Conway, 2018; a priori: HEI-2010 | ▲ ▲ | V | V | ▲ ▲ | | | ▲ | | ▼ | ▲ pro | F, pro | F, pro | F, pro | | ▲ | | | ▼ | SB | ▲ | | ▼ | | ▼ Na^+^
den Braver, 2019; a priori: DHD 15 | ▲ | | ▲ | ▲ | SB | ▲ | ▲ | | ▼ | ▲ | | ▼ R ▼ P | | | | | | ▼ | | | | ▼ | ▼ | | ▲ T
Dominguez, 2015; a priori: DDS | ▲ | | | ▲ | | ▲ | ▲ | | | | | ▼ R ▼ P | | | | ▲ | | ▼ | | ▲ | | | ◄ | | ▲ C | ▲
Dow, 2019; a priori: ADG-13 | ▲ | | V | ▲ | | L, pro | | ▲ | | L, pro | | | L, pro | L, pr o | ▲ | | | | | | | | ◄
Duan, 2021; RRR: DP ♀ | ▼ | | | ▼ | ▲ | ▼ | | ▼ | | ▼ ▼ | | | | ▼ | ▼ | ▼ | ▼ | ▲ | ▲ | | | | | | ▼ T
Duan, 2021; RRR: DP ♂ | ▼ | | | ▼ | ▲ | ▼ | | ▼ | | | | | | | ▼ | ▼ | ▼ | ▲ | ▲ | | | | | | ▲ C | ▲ | ▼
Duan 2022_L; a priori: LLDS | ▲ | | ▲ | ▲ | | LN | ▲ | | | ▲ | | ▼ RP | | | ▲ | | | ▼ | | ▲ | | ▼ | | | ▲
Duan, 2022 UP; F/C: ‘warm savory snack’ | | ▲ | | | | | | | | | | | | | | | | | | | | | | | | ▲
Duan, 2022 UP; F/C: ‘cold savory snack’ | | | | | | | | | | | | ▲ P | | | ▲ ch | | | | | | | | | | | ▲
Duan, 2022 UP; F/C: ‘traditional Dutch cuisine’ | | | | | | | | ▲ | | | | ▲ P | | | | | | | | | | | | | | ▲
Duan, 2022 UP; F/C: ‘sweet snack’ | | | | | | | | | | | | | | | | | | | ▲
Duan, 2022 UP; a priori: UPF, Nova4 | | | | | | | | ▲ | | | | | | | | ▲ | D, not ch | ▲ | | | | | | | SB
Eguaras, 2017; a priori: MDS | ▲ | | ▲ | ▲ | | ▲ | | ▲ | | ▲ | | ▼ RP | | | ▼ | | | | | ▲ UF:SF | | UF: SF | ◄
Ericson, 2018; a priori: DRS, eDRS | | | | | | | ▼ | | | | | ▲ RP | | | | | | ▲ | | | | | | | ▼
Ericson, 2018; a priori: DRS, eDRS | ▼ | | | FV | | | ▼ | | | ▼ | | ▲ RP | | | ▼ | | | ▲ | | | | | | | ▼
Ericson, 2019; F/C: Health-Conscious’ | ▲ | | | ▲ | | | ▲ | ▲ | ▼ | ▲ | | ▼ RP | | | ▲ | ▲ | | ▼
Ericson, 2019; F/C: Low Fat’ | | | | | | | | | | | | | | | | ▲ | | | | | ▲ | ▼
Ericson, 2019; F/C: Dressing-Vegetables’ | ▲ | ◄ | | | | | | ▲ | | | | | ▲ | | ▲ ch | | | | ▼ | ▲ | | | | ▲ | | ▲
Esfandiar, 2022; a priori: HEI2015 | ▲ ▲ | V | V | ▲ ▲ | | | ▲ | | ▼ | ▲ pro | F, pro | F, pro | F, pro | | ▲ | | | ▼ | SB | ▲ UF:SF | | ▼ | | ▼ Na^+^
Esfandiar, 2022; a priori: MDS | ▲ | | ▲ | ▲ | | ▲ | | ▲ | | ▲ | | ▼ RP | | | ▼ | | | | | ▲ UF:SF | | | ◄
Esfandiar, 2022; a priori: DASH | ▲ | X | ▲ | ▲ | Fr | LN | ▲ | | | | | ▼ RP | | | | ▲ | | ▼ | | | | | | ▼ Na^+^
Farhadnejad, 2020; a priori: EDIH | ▼ | ▲ fried | | ▼ | | | | | | ▲ | | ▲ R ▲ P | ▲ | ▲ | | ▲ | ▼ | ▲ | | | ▲ | | ▼w | | ▼ C | ▲
Farhadnejad, 2020; a priori: EDIR | ▼ | ▲ fried | | ▼ | ▲ | ▼ | | ▲ | | ▲ | | ▲ R ▲ P | | | | | ▼ | ▲ | | | ▲ | | | | ▼ C | | ▲
Filippatos, 2016; a priori: MedDietScore | ▲ | ▲ | ▲ | ▲ | | | ▲ | | | ▲ | | ▼ RP | ▼ | | | | ▼ | | | ▲ oo | | | ▼
Freisling, 2020; a priori: rMED | ▲ | X | ▲ | ▲ | | Fr | ▲ | G | G | ▲ | | ▼ RP | | | | | | | | ▲ oo | | | ◄
Fung, 2021; a priori: GDQS,m | ▲ ▲ ▲ ▲ | ▼ | ▲ | ▲ ▲ ▲ | ▼ | ▲ | ▲ | | ▼ | ▲ | FS | ▼ R ▼ P | ▲ | ▲ | | ▲ | ▼ | ▼ | ▼ | ▲ | | | | | | ▼
Fung, 2021; a priori: aHEI2010 | ▲ | X | ▲ | ▲ | SB | LN | ▲ | | | | | ▼ RP | | | | | | ▼ | | ▲ ▲ | ▼ Tr | | ◄ | ▼ Na^+^
Fung, 2021; a priori: MDD-W | ▲ ▲ ▲ | | | ▲ FrV ▲ | | ▲ | | V | | | | ▲ | M | ▲ | ▲
Galbete, 2018; a priori: Nordic diet score | ▲ | ▲ ▲ | | ▲ | | | ▲ | | | ▲ | | | | | | ▲ | | | | | ▲
Galbete, 2018; a priori: LitMDS | ▲ | ▼ | ▲ | ▲ | | Fr | | ▲ | | ▲ | | ▼ | M | ▲ | ▼ | | | | ▼ | ▲ oo | | | ◄
Galbete, 2018; a priori: PyrMDS | ▲ | ▼ | ▲ | ▲ | | ▲ | | ▲ | | ▲ | | ▼ R ▼ P | ▲ | ▲ | ▲ | | | | ▼ | ▲ oo | | | ▼
Gao, 2022; RRR: DP1 | ▼ | | | ▼ | | | | | ▲ | | | | | | | | | | ▲ | | | ▲ | | | | ▲
Gao, 2022; RRR: DP2 | | | | | ▲ | | | | | | | | | | | | ▼ | ▲ | | | | ▼ | | | | ▲
Glenn, 2021_W; a priori: aMED | ▲ | X | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼ RP | | | | | | | | ▲ UF:SF | | UF: SF | ◄
Glenn, 2021_W; a priori: DASH | ▲ | X | ▲ | ▲ | Fr | LN | ▲ | | | | | ▼ RP | | | | ▲ | | ▼ | | | | | | ▼ Na^+^
Glenn, 2021_P; a priori: DASH | ▲ | X | ▲ | ▲ | Fr | LN | ▲ | | | | | ▼ RP | | | | ▲ | | ▼ | | | | | | ▼ Na^+^
Hirahatake, 2019; a priori: aPDQS | ▲ | ◄ | ▲ | ▲ | ◄ | ▲ | ▲ | | ◄ | ▲ | ◄ | ▼ | ◄ | ◄ | | ▲ | ▼ | ▼ | ▼ | ▲ VO | ◄ | ▼ | ▲ | ▼ | ▲ | ◄ ◄ ◄ ◄ ◄ | ▼▼ ▼ ▼
Hirahatake, 2019; a priori: DGA-2015 | ▲ | | ▲ | ▲ | | LN | ▲ | | ▼ | ▲ | FS | ▼ RP | X | | | ▲ | | ▼ | SB | | X | | ◄ | ▼ Na^+^ | X
Hirahatake, 2019; a priori: Paleo | ▲ | | | ▲ | | ▲ | | ▼ | ▼G | | | ▼ RP | ▲ | | ▼ | | | | | | | | ▼ | ▼ Na^+^ | | ▲
Hirahatake, 2019; a priori: Empty Calories | | ▲ fried | | | ▲ | | | | ▲ ▲ | | | | | | ▲ AS | | | ▲ | ▲ | | ▲ | ▲ | ▲ | ▲ | | ▲ ▲
Hlaing-Hlaing, 2021; a priori: MDS | ▲ | | ▲ | ▲ | | ▲ | | ▲ | | ▲ | | ▼ RP | | | ▼ | | | | | ▲ UF:SF | | UF: SF | ◄
Hlaing-Hlaing, 2021; a priori: aHEI-2010 | ▲ | X | ▲ | ▲ | SB | LN | ▲ | | | | | ▼ RP | | | | | | ▼ | | ▲ ▲ | ▼ Tr | | ◄ | ▼ Na^+^
Hlaing-Hlaing, 2021; a priori: HEIFA-2013 | ▲ ▲ | | ▲ | ▲ ▲ | | Fat | ▲ | ▲ | | ▲ | | ▼ P | ◄ M, L | | ◄ D, L | | | ▼ | SB | ▲ | | ▼
Hlaing-Hlaing, 2022; a priori: aHEI-2010 | ▲ | X | ▲ | ▲ | SB | LN | ▲ | | | | | ▼ RP | | | | | | ▼ | | ▲ ▲ | ▼ Tr | | ◄ | ▼ Na^+^
Hodge, 2021; a priori: aHEI2010 | ▲ | X | ▲ | ▲ | SB | LN | ▲ | | | | | ▼ RP | | | | | | ▼ | | ▲ ▲ | ▼ Tr | | ◄ | ▼ Na^+^
Hodge, 2021; a priori: MDS | ▲ | | ▲ | ▲ | | ▲ | | ▲ | | ▲ | | ▼ RP | | | ▼ | | | | | ▲ UF:SF | | UF: SF | ◄
Jacobs, 2015; a priori: HEI-2010 | ▲ ▲ | V | V | ▲ ▲ | | | ▲ | | ▼ | ▲ pro | F, pro | F, pro | F, pro | | ▲ | | | ▼ | SB | ▲ | | ▼ | | ▼ Na^+^
Jacobs, 2015; a priori: aHEI2010 | ▲ | X | ▲ | ▲ | SB | LN | ▲ | | | | | ▼ RP | | | | | | ▼ | | ▲ ▲ | ▼ Tr | | ◄ | ▼ Na^+^
Jacobs, 2015; a priori: aMED | ▲ | X | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼ RP | | | | | | | | ▲ UF:SF | | UF: SF | ◄
Jacobs, 2015; a priori: DASH | ▲ | X | ▲ | ▲ | Fr | LN | ▲ | | | | | ▼ RP | | | | ▲ | | ▼ | | | | | | ▼ Na^+^
Jacobs, 2017_A; a priori: HEI2010 | ▲ ▲ | V | V | ▲ ▲ | | | ▲ | | ▼ | ▲ pro | F, pro | F, pro | F, pro | | ▲ | | | ▼ | SB | ▲ | | ▼ | | ▼ Na^+^
Jacobs, 2017_A; a priori: aHEI2010 | ▲ | X | ▲ | ▲ | SB | LN | ▲ | | | | | ▼ RP | | | | | | ▼ | | ▲ ▲ | ▼ Tr | | ◄ | ▼ Na^+^
Jacobs, 2017_A; a priori: aMED | ▲ | X | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼ RP | | | | | | | | ▲ UF:SF | | UF: SF | ◄
Jacobs, 2017_A; a priori: DASH | ▲ | X | ▲ | ▲ | Fr | LN | ▲ | | | | | ▼ RP | | | | ▲ | | ▼ | | | | | | ▼ Na^+^
Jacobs, 2017_D; RRR: Combined diet of all | ▲ | | | ▲ | | | ▲ | | ▼ | | | ▼ RP | | | | ▲ | | ▼ | | | | | | | | ▼
Jannasch, 2019; F/C: France DP1 | ▲ | ▲ | | | | | | | | | | ▲R | ▲
Jannasch, 2019; F/C: France DP2 | | | | ▲ | | ▲ | | | | ▲ | | ▲P | | ▲ | | | | | ▲ | | | | ▲ | | ▲C
Jannasch, 2019; F/C: Italy DP1 | ▲ | | ▲ | | | | | | | ▲ | | | | | | | | | | ▲
Jannasch, 2019; F/C: Italy DP2 | | | | | | | | ▲ | | | | ▲RP | | | | | | | ▲ | | ▲
Jannasch, 2019; F/C: Spain DP1 | | ▲ | ▲ | | | | | ▲ | | | | ▲RP | | ▲ | | | | | | ▲ | | | ▲
Jannasch, 2019; F/C: Spain DP2 | ▲ | ▲ | | ▲
Jannasch, 2019; F/C: UK Norfolk DP1 | ▲ | ▲ | | ▲ | | | | ▲
Jannasch, 2019; F/C: UK Norfolk DP2 | | ▲ | | | | | | | | | | ▲P | | | | | | | ▲ | ▲ | | | | | ▲T
Jannasch, 2019; F/C: UK Oxford DP1 | ▲ | ▲ | ▲ | ▲
Jannasch, 2019; F/C: UK Oxford DP2 | | ▲ | | | | | | | | ▲ | | ▲RP | ▲ | | | | | | | ▲ | | | | | | ▲
Jannasch, 2019; F/C: Netherlands, DP1 | | ▲ | | | | | | ▲ | | | | ▲RP | | | | | | | ▲ | | ▲
Jannasch, 2019; F/C: Netherlands, DP2 | ▲ | | | ▲ | | | | ▲ | | | | | ▲ | | | | | | | ▲ | ▲
Jannasch, 2019; F/C: Germany, DP1 | ▲ | ▲ | | ▲ | | | | | | | | | | | | | | | | ▲
Jannasch, 2019; F/C: Germany, DP2 | | ▲ | | | | | | | | | | ▲RP | ▲ | | | | | | | | ▲ | | ▲B | | | ▲
Jannasch, 2019; F/C: Sweden, DP1 | | ▲ | | | | | | ▲ | | | | ▲P | | | | | | ▼ | ▲ | | ▲
Jannasch, 2019; F/C: Sweden, DP2 | | | | | | | | | | | | | | | | | | | | | | | ▲w
Jannasch, 2019; F/C: Denmark, DP1 | ▲ | ▲ | ▲ | ▲ | | | | ▲ | | ▲ | | | ▲ | | | | | | | ▲
Jannasch, 2019; F/C: Denmark, DP2 | | ▲ | | | | | | ▲ | | | | ▲RP | | | | | | | | | ▲ | | | | | ▲
Jin, 2021; a priori: EDIP | ▲ ▲ | | | | ▲ | | | | ▼ | ▼ | | ▼ P ▼ R ▼ | | | | | | ▼ | | | | | | | ▲ T ▲ C | ▲ ▲ | ▼ V ▼ V
Jin, 2021; a priori: EDIH | ▲ | ▲ fried | | ▼ | | | | | | ▲ | | ▲ R ▲ P | ▲ | ▲ | | ▲ | ▼ | ▲ | | | ▲ | | ▼w | | ▼ C | ▲ | ▼ V
Kanerva, 2014; a priori: BSD | ▲ | X | ▲ | ▲ | | | ▲ | | | ▲ | | ▼ RP | | | | | | | | ▲ UF:SF | | UF: SF | ◄
Kesse-Guyot, 2021; a priori: PNNS-GS2 | ▲ | ◄ | ▲ | V | | ▲ | ▲ | ◄ | | ◄ | ▲ | ▼R ▼P | ◄ | ◄ | ▲ | | | ▼ | ▼ | ▲ | | ▼ | ▼ | ▼ Na^+^
Khalili-Moghadam, 2019; a priori: MDS | ▲ | | ▲ | ▲ | | ▲ | | ▲ | | ▲ | | ▼ RP | | | ▼ | | | | | ▲ UF:SF | | UF: SF | ◄
Kim & Giovannucci, 2022; a priori: PDI | ▲ | ▲ | ▲ | ▲ | ▲ | ▲ | ▲ | | ▲ | ▼ | FS | ▼ | M | ▼ | ▼ | | | ▲ | ▲ | Fr | | ▼ | | | ▲ | ▼ AP
Kim & Giovannucci, 2022; a priori: hPDI | ▲ | ▼ | ▲ | ▲ | ▼ | ▲ | ▲ | | ▼ | ▼ | FS | ▼ | M | ▼ | ▼ | | | ▼ | ▼ | Fr | | ▼ | | | ▲ | ▼ AP
Kim & Giovannucci, 2022; a priori: uPDI | ▼ | ▲ | ▼ | ▼ | ▲ SB | ▼ | ▼ | | ▲ | ▼ | FS | ▼ | M | ▼ | ▼ | | | ▲ | ▲ | Fr | | ▼ | | | ▼ | ▼ AP
Koloverou, 2016_A; a priori: MedDietScore | ▲ | ▲ | ▲ | ▲ | | | ▲ | | | ▲ | | ▼ RP | ▼ | | | | ▼ | | ▼ | ▲ oo | | | ▼
Koloverou, 2016 D; F/C: Factor 1 | | ▲ | | | | | | | | | | ▲ | ▲
Koloverou, 2016 D; F/C: Factor 2 | ▲ | | ▲ | ▲ | | | | ▲
Koloverou, 2016 D; F/C: Factor 3 | | | | | | | | | | | | ▲P | | | ▲ch
Koloverou, 2016 D; F/C: Factor 4 | | | | | | | | | | ▲
Koloverou, 2016 D; F/C: Factor 5 | | | | | | ▲ | | | | | | | | | | | | | ▲
Koloverou, 2016 D; F/C: Factor 6 | | | | | | | | ▲ | | | | | | | ▲
Kroger (Interact Consortium), 2014; a priori: aHEI (2000) | ▲ | X | ▲ | ▲ | | LN | | | | | | W:R | ▲ W:R | | | | | | | ▲ UF:SF | ▼ Tr | UF: SF | ◄ | | | ▲ ▲
Kroger (Interact Consortium), 2014; a priori: DASH 1995 | ▲ | | ▲ | ▲ | | LN | ▲ | | | M | | ▼ | M | | ▲ | | | | ▼ | | ▼
Kroger(Interact Consortium), 2014; RRR, 1 | ▲ | | | | | | | | ▼ | | | ▼ P | | | | | | ▼ | | | | | ▲w | | ▲ C | ▼
Kroger(Interact Consortium), 2014; RRR, 2 | | | ▼ | ▲ | | | | ▼ | | | | ▼ | ▼ | | | | | ▼ | | | | | ▼ B
Kroger(Interact Consortium), 2014; RRR, 3 | | | | | | | | ▲ | ▲ | | | ▼ P | | | | | | ▼ | ▲ | | | | | ▼ | | ▼ | ▲
Lacoppidan, 2015; a priori: HNFI | ▲ | ▲ | | ▲ | | | ▲ ▲ | | | ▲
Langmann, 2023; a priori: EAT-LR | ▲ | ◄ | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼ | | ◄ | ◄ | | | ▼ | SB | ▲ | ◄ | ▼
Langmann, 2023; a priori: aHEI-2010 | ▲ | X | ▲ | ▲ | SB | LN | ▲ | | | | | ▼ RP | | | | | | ▼ | | ▲ ▲ | ▼ Tr | | ◄ | ▼ Na^+^
Laouali, 2021; a priori: PDI | ▲ | ▲ | ▲ | ▲ | ▲ | ▲ | ▲ | | ▲ | ▼ | FS | ▼ | M | ▼ | ▼ | | | ▲ | ▲ | ▲ | | ▼ | | | ▲ | ▼ AP
Laouali, 2021; a priori: hPDI | ▲ | ▼ | ▲ | ▲ | ▼ | ▲ | ▲ | | ▼ | ▼ | FS | ▼ | M | ▼ | ▼ | | | ▼ | ▼ | ▲ | | ▼ | | | ▲ | ▼ AP
Laouali, 2021; a priori: uPDI | ▼ | ▲ | ▼ | ▼ | ▲ SB | ▼ | ▼ | | ▲ | ▼ | FS | ▼ | M | ▼ | ▼ | | | ▲ | ▲ | ▼ | | ▼ | | | ▼ | ▼ AP
Lee, 2019 A; RRR: ♂ | | | ▲ soy | | | ▲ | | | | ▲ | | ▲ R | ▲ | | | | | ▼ | | | | | | | ▲ C | ▲ | ▼ M, P
Lee, 2019 A; RRR: ♀ | | | | ▲ | | | | ▼ | ▲ | ▼ | ▼ | | ▼ | | | | | | ▼ | | | | | | | ▲
Lee, 2019 I; F/C: ‘Prudent’ | ▲ | ▲ | ▲ | ▲ | | | | | | ▲ | ▲ | | | | ▲
Lee, 2019 I; F/C: ‘Fatty fish, meat, flour-based’ | | | | | | | | ▲ | | ▲ | ▲ | ▲ RP | ▲ | | ▲ | | | ▲ | ▲ | | | | | | | ▲ ▲
Lee, 2019 I; F/C: ‘Coffee Sweets’ | | | | | | | | | | | | | | | | | | | ▲ | ▲ | | | | | ▲C
Lee, 2019 I; F/C: ‘White Rice’ | | | | | | | ▲♂ ▼♀ | | ▲♀ ▼♂
Lee, 2020; a priori: EDIP | ▲ ▲ | | | | ▲ | | | | ▼ | ▼ | | ▼ P ▼ R ▼ | | | | | | ▼ | | | | | | | ▲ T ▲ C | ▲ ▲ | ▼ V ▼ V
Lee, 2020; a priori: EDIH | ▼ | ▲ fried | | ▼ | | | | | | ▲ | | ▲ R ▲ P | ▲ | ▲ | | ▲ | ▼ | ▲ | | | ▲ | | ▼w | | ▼ C | ▲ | ▲V
Ley, 2016; a priori: aHEI2010 | ▲ | X | ▲ | ▲ | SB | LN | ▲ | | | | | ▼ RP | | | | | | ▼ | | ▲ ▲ | ▼ Tr | | ◄ | ▼ Na^+^
Llavero-Valero, 2021; a priori: UPF, Nova4 | ▲ UP | ▲ | V | | SB | | | ▲ UP | ▲ | | | ▲ RP | M, P | | ▲ UP | ▲ | ▲ | ▲ | ▲ | ▲ | | ▲ | ▲ | ▲ | SB | ▲
Lopez, 2022; a priori: EAT-LR | ▲ | ◄ | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼ | | ◄ | ◄ | | | ▼ | SB | ▲ | ◄ | ▼
Ma, 2022; PCA: typical Japanese’ | ▲ | | ▲ | ▲ | ▼ | | | ▼ | ▲ | ▲ | | ◄ | ◄ RP | | ◄ | | | | | | | | | | | ▲ | ▼ V
Ma, 2022; PCA: Juice’ | | | ▲ | ▲ | ▲ | | | ▲ | | | | ▼ R | ◄ | | ▲ | | | | | | | | | | | ▲
Ma, 2022; PCA: Meat’ | | | | | | | | ▲ ♀ | | | | ▲ RP | ▲
Maldonado ; PCA: ‘Burgers, Fries, Soft Drinks’ | | ▲ FF | | | | | | | | | | | | | | | | ▲ | | | | | | | | ▲ ▲
Maldonado ; PCA: ‘White Rice, Beans, Red Meats’ | | | | | | | | | ▲ | | | ▲ RP
Maldonado ; PCA: ‘Fish & Whole Grain’ | ▲ | | | | | | ▲ | | | ▲ | | | ▲
Maldonado ; PCA: ‘Cheese & Sweets’ | | | | | | | | | ▼ | | | | | | ▲ | | | | ▲ | | | | | | ▲ | ▲ ▲
Maldonado ; PCA: ‘Stew & Corn’ | | | | | | | | | | | | | ▼ | | ▲ | | | | | | | | | | | ▲ ▲
Mandalazi, 2016; a priori: DQI-SNR | ▲ | | | V | | | | | | ▲ | FS | | | | | | | | ▼ | ◄ | | ▼ | | | | ◄
Markanti, 2021; a priori: D-DGI | ▲ | | | V | | | ▲ | | | ▲ | | ▼ RP | | | | | | | ▼ | | | ▼
Mattei, 2017; a priori: AHA-DS | ▲ | | | ▲ | Fr | | ▲ | | | ▲ | | | | | | | | ▼ | SB | | ▼ | ▼ | ◄ | ▼ Na^+^
Mattei, 2017; a priori: aHEI2010 | ▲ | | ▲ | ▲ | SB | LN | ▲ | | | | | ▼ RP | | | | | | ▼ | | ▲ ▲ | | ▼ | ◄ | ▼ Na^+^
Mattei, 2017; a priori: HEI-2005 | ▲ ▲ | | ▲ | ▲ ▲ | | | ▲ | ▲ | G | | | ▲ | | | ▲ | | | ▼ | SB | ▲ | | AS | AS | ▼ Na^+^
Mattei, 2017; a priori: MDS | ▲ | | ▲ | ▲ | | ▲ | | ▲ | | ▲ | | ▼ RP | | | ▼ | | | | | ▲ UF:SF | | UF: SF | ◄
Mattei, 2017; a priori: DASH, m | ▲ | X | ▲ | ▲ | Fr | LN | ▲ | | | | | ▼ RP | | | ▲ | | | ▼ | | | | | | ▼ Na^+^
Merino, 2022; a priori: DASH | ▲ | X | ▲ | ▲ | Fr | LN | ▲ | | | | | ▼ RP | | | | ▲ | | ▼ | | | | | | ▼ Na^+^
Merino, 2022; a priori: aHEI2010 | ▲ | X | ▲ | ▲ | | LN | ▲ | | | | | ▼ RP | | | | ▲ | | ▼ | | ▲ ▲ | ▼ Tr | | ◄ | ▼ Na^+^
Neuhouser, 2022; a priori: HEI-2010 | ▲ ▲ | V | V | ▲ ▲ | | | ▲ | | ▼ | ▲ pro | F, pro | F, pro | F, pro | | ▲ | | | ▼ | SB | ▲ | | ▼ | | ▼ Na^+^
O’Connor, 2020; a priori: aMED | ▲ | X | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼ RP | | | | | | | | ▲ UF:SF | | UF: SF | ◄
Otto, 2015; a priori: aHEI | ▲ | X | ▲ | ▲ | | LN | | | | | | W:R | ▲ W:R | | | | | | | ▲ UF:SF | ▼ Tr | UF: SF | ◄ | | | ▲
Otto, 2015; a priori: aDASH | ▲ | X | ▲ | ▲ | Fr | ▲ | ▲ | | | | | ▼ RP | | | | ▲ | | ▼ | | ▲ | | | | ▼ Na^+^
Otto, 2015; a priori: aPDQS | ▲ | ◄ | ▲ | ▲ | ◄ | ▲ | ▲ | | ◄ | ▲ | ◄ | ▼ | ◄ | ◄ | | ▲ | ▼ | ▼ | ▼ | ▲ | ◄ | ▼ | ▲ | ▼ | ▲ | ◄◄ ◄ ◄ ◄ | ▼ ▼ ▼ ▼
Pant, 2023; a priori: UPF, Nova4 | | ▲ UP | | | | | | ▲ ▲ | ▲ ▲ | | | ▲P | | | ▲ ▲ AS | | | | ▲ | | ▲ | | | | | ▲ ▲
Papier, 2019; Other: Regular meat eater; | ▼ | | ▼ | ▼ | | ▼ | | | | | | ▲ RP | ▲ | | ▼ ch | ▲ milk | Milk | | ▲ | ▲ | ▲ | ▲ | | | | ▼ pro
Papier, 2019; Other: Low meat eater; | ▲ | | ▲ | ▲ | | ▲ | | | | | | ▼ RP | ▼ | | ▲ ch | ▼ milk | Milk | | ▼ | ▼ | ▼ | ▼ | | | | ▲ pro
Papier, 2019; Other: Fish eater’ | ▲ | | ▲ | ▲ | | ▲ | | | | ▲ | | | | | ▲ ch | ▼ milk | Milk | | ▼ | ▼ | ▼ | ▼ | | | | ▲ pro
Papier, 2019; Other: Vegetarian’ | ▲ | | ▲ | ▲ | | ▲ | | | | | | | | ▲ | ▲ ch | ▼ milk | Milk | | ▼ | ▼ | ▼ | ▼ | | | | ▲ pro
Papier, 2019; Other: Vegan’ | ▲ | | ▲ | ▲ | | ▲ | | | | | | | | | | | | | ▼ | ▼ | ▼ | ▼
Pastorino, 2016; RRR: No name | ▼ | ▲ fried | | ▼ | | | ▼ | | ▲ | | | ▲ P | | | | ▼ | | | ▲ | | | ▲
Qiao, 2014; a priori: aHEI (2000) | ▲ | | ▲ | ▲ | | LN | | | | | | W: R | ▲ W: R | | | | | | | ▲ UF:SF | ▼ Tr | UF: SF | ◄ | | | ▲
Rajaobelina, 2019; a priori MDS, modified | ▲ | | ▲ | ▲ | | ▲ | | ▲ | | ▲ | FS | ▼ RP | | | ▼ | | | | | ▲ oo | | | ◄
Rayner, 2020; a priori: LCDs | ▲ | | | ▼ | ▼ | | ▼ | ▼▼ | ▲ | | | | | | | | | ▼ | SB | ▲ ▲ | ▲ ▲ | ▲ | | | | ▼▼ | ▲ pro
Riboldi, 2022; a priori: IFI | | | | ▼ | ▲ NS ▲ SB | ▼ | ▼ | | | | ▲ | ▲R ▲P ▲ ▲ | ▼ | | | | | ▲ ▲ ▲ C | | | | ▼ | ▼ w | | SB | ▼
Ruiz-Estigarribia, 2020; a priori: MDS | ▲ | | ▲ | ▲ | | ▲ | | ▲ | | ▲ | | ▼ RP | | | ▼ | | | | | ▲ UF:SF | | UF: SF | ◄
Sali, 2020; a priori: LCS | ▲ | | ▲ | ▼ | | LN | ▼ | ▼ | | | | ▲ RP | | | ▲
Satija, 2016; a priori: PDI | ▲ | ▲ | ▲ | ▲ | ▲ | ▲ | ▲ | | ▲ | ▼ | FS | ▼ | M | ▼ | ▼ | | | ▲ | ▲ | ▲ | | ▼ | | | ▲ | ▼ AP
Satija, 2016; a priori: hPDI | ▲ | ▼ | ▲ | ▲ | ▼ | ▲ | ▲ | | ▼ | ▼ | FS | ▼ | M | ▼ | ▼ | | | ▼ | ▼ | ▲ VO | | ▼ | | | ▲ | ▼ AP
Seah, 2019; RRR: No name | ▲ ▲ | | ▲ soy | ▲ | | | | ▲ | ▼ | ▲ | | ▼ ▼ | M | ▼ | ▲ | | | ▼ | | | ▲ | | ▼ | | ▲ T
Shah, 2021; a priori: Paleo | ▲▲ | | | ▲ | | ▲ | | ▼ | ▼ | ▲ | | ▼ RP | ▲ | | ▼ | | | | | | | | ▼ | ▼ Na^+^ | | ▲
Shan, 2018 BMJ; a priori: aHEI2010 | ▲ | X | ▲ | ▲ | SB | LN | ▲ | | | | | ▼ RP | | | | | | ▼ | | ▲ ▲ | ▼ Tr | | ◄ | ▼ Na^+^
Song, 2019; RRR: ♂ | | | | ▲ | | ▼ | | ▲ | | | ▲ fer | | ▼ | | | | | | ▼ | | | | | FS
Song, 2019; RRR: ♀ | | | | | | ▼ | | | | | | ▲ ▲ | ▲ | | ▼
Song, 2021; a priori: ‘highquality’ score | ▲ | | | ▲ | | | | | | ▲ | FS | ▼ P | ◄ NP
Srour, 2020; a priori: UPF, Nova4 | | | | ▲ UP | ▲ UP | | | ▲ UP | ▲ UP | | | ▲ UP | ▲ UP | | ▲ UP | ▲ UP | ▲ UP | ▲ UP | ▲ UP | | ▲ UP | | | ▲ UP | SB | ▲
Tait, 2020; a priori: HEI-C | ▲ ▲ ▲ | | M | ▲ | | | ▲ | ▲ | | | | ▲ | M, MA | | ▲ D, DA | | | | | ▲ | | ▼ | | ▼ Na^+^ | | ▼
Tertsunen, 2021; a priori: mBSD | ▲ | V | V | ▲ | | | ▲ | | | ▲ | | ▼ RP | | | | ▲ | | | | ▲ UF:SF | ▼ | UF: SF | ◄
Teymoori, 2021; a priori: DIS | ▲▲ | | | | ▲ | | | | ▼ | ▼ | | ▼ P ▼ R ▼ | | | | | | ▼ | | | | | | | ▲ T ▲ C | ▲ ▲ | ▼V▼V
Teymoori, 2021; a priori: EDIP | ▲▲ | | | | ▲ | | | | ▼ | ▼ | | ▼ P ▼ R ▼ | | | | | | ▼ | | | | | | | ▲ T ▲ C | ▲ ▲ | ▼V▼V
Teymoori, 2023; a priori: DIR
Tison, 2022; a priori: MDS | ▲ | | ▲ | ▲ | | ▲ | | ▲ | | ▲ | | ▼ RP | | | ▼ | | | | | ▲ UF:SF | | | ◄
Tison, 2022; a priori: DASH | ▲ | X | ▲ | ▲ | Fr | LN | ▲ | | | | | ▼ RP | | | | ▲ | | ▼ | | | | | | ▼ Na^+^
Tison, 2022; a priori: MIND | ▲ | ▲ | ▲ | ▲ | | ▲ | ▲ | | | | ▲ | ▼ R | ▲ | | ▼ ch | | | | | ▲ oo | | ▼ | ▲ w | | | ▼
Tison, 2022; F/C: ‘Plantbased’ | ▲ | | ▲ | ▲ | | | | | | ▲ | | | ▲
Tison, 2022; F/C: ‘Southern’ | | | | | | | | ▲ | | | | ▲ P | | ▲ | | | ▲ | ▲ | | | ▲
Ushula, 2022; F/C : ‘Western’ | | | | | | | ▼ | | | | | ▲ | ▲ | | | ▼ | ▲ | | | | | | | | | ▲
Ushula, 2022; F/C: ‘Prudent’ | ▲ | | | ▲ | | ▲ | | ▲ | ▼ | | | | | | | ▲ | | | | | | | | | | ▲
Vinke, 2020; a priori: LLDS | ▲ | | ▲ | ▲ | | LN | ▲ | | | ▲ | | ▼ RP | | | | ▲ | | ▼ | | ▲ | | ▼ | | | ▲
Voortman, 2017; a priori: DDG-15 | ▲ | | ▲ | ▲ | | ▲ | ▲ | | ▼ | ▲ | | ▼ R ▼ P | | | ▲ | | | ▼ | | ▲ | | ▼ | ▼ | ▼ Na^+^ | ▲ T
Walsh, 2021; PCA: Western’ | ▲▲ | ▲ | | | | | | ▲ | ▲ | | | ▲ RP | ▲ | ▲ fried | | | | ▲ | ▲ | | ▲ | ▲ | ▲ | ▲ | | ▲ ▲
Walsh, 2021; PCA: Prudent’ | ▲ | | ▲ | ▲ | | ▲ | | | | ▲ | | | | | ▲ | | | | | | | | | | | ▲ ▲
Wang F, 2022; a priori: PDI | ▲ | ▲ | ▲ | ▲ | ▲ | ▲ | ▲ | | ▲ | ▼ | FS | ▼ | M | ▼ | ▼ | | | ▲ | ▲ | ▲ | | ▼ | | | ▲ | ▼ AP
Wang F, 2022; a priori: hPDI | ▲ | ▼ | ▲ | ▲ | ▼ | ▲ | ▲ | | ▼ | ▼ | FS | ▼ | M | ▼ | ▼ | | | ▼ | ▼ | ▲ | | ▼ | | | ▲ | ▼ AP
Wang F, 2022; a priori: uPDI | ▼ | ▲ | ▼ | ▼ | ▲ SB | ▼ | ▼ | | ▲ | ▼ | FS | ▼ | M | ▼ | ▼ | | | ▲ | ▲ | ▼ | | ▼ | | | ▼ | ▼ AP
Wang P, 2023; a priori: aHEI2010 | ▲ | | ▲ | ▲ | SB | LN | ▲ | | | | | ▼ RP | | | | | | ▼ | | ▲ ▲ | | ▼ | ◄ | ▼ Na^+^
Wang P, 2023; a priori: aMED | ▲ | | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼ RP | | | | | | | | ▲ UF:SF | | UF: SF | ◄
Wang P, 2023; a priori: hPDI | ▲ | ▼ | ▲ | ▲ | ▼ | ▲ | ▲ | | ▼ | ▼ | FS | ▼ | M | ▼ | ▼ | | | ▼ | ▼ | ▲ | | ▼ | | | ▲ | ▼ AP
Wang P, 2023; a priori: DASH | ▲ | | ▲ | ▲ | Fr | LN | ▲ | | | | | ▼ RP | | | | ▲ | | ▼ | | | | | | ▼ Na^+^
Wang P, 2023; a priori: DRRD | | | | ▲ | SB | ▲ | | | | | | ▼ R | | | | | | ▼ | | ▲ UF:SF | ▼ Tr | UF: SF | | | ▲ C | ▲ | ▼
Wang P, 2023; a priori: WCRF AICR diet score | ▲ | | ▲ | ▲ | | | ▲ | | | | | ▼ RP | | | | | | ▼ | | | | | ◄ | | | ▼ ▼
Wang P, 2023; a priori: EDIH | ▼ | ▲ fried | | ▼ | | | | | | ▲ | | ▲ R ▲ P | ▲ | ▲ | | ▲ | ▼ | ▲ | | | ▲ | | ▼w | | ▼ C | ▲ ▲ V
Wang P, 2023; a priori: EDIP | ▲▲ | | | | ▲ | | | | ▼ | ▼ | | ▼ P ▼ R ▼ | | | | | | ▼ | | | | | | | ▲ T ▲ C | ▲ ▲ | ▼V▼V
Wang Y, 2022; PCA: Junk food’ | | | | | | | | | | | | | | | | | | ▲ | ▲ | | | | | | | ▲
Wang Y, 2022; PCA: Vegetable-grain’ | ▲ | | | | | | | ▲
Xu, 2020; a priori: HEI-2015 | ▲▲ | V | V | ▲ ▲ | | | ▲ | | ▼ | ▲ pro | F, pro | F, pro | F, pro | | ▲ | | | ▼ | SB | ▲ UF:SF | | ▼ | | ▼ Na^+^
Xu, 2020; a priori: aHEI2010 | ▲ | | ▲ | ▲ | SB | LN | ▲ | | | | | ▼ RP | | | | | | ▼ | | ▲ ▲ | | ▼ | ◄ | ▼ Na^+^
Xu, 2022; a priori: EAT-LR | ▲ | ◄ | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼ | | ◄ | ◄ | | | ▼ | SB | ▲ | ◄ | ▼
Yu, 2022; a priori: MDS | ▲ | | ▲ | ▲ | | ▲ | | ▲ | | ▲ | | ▼ RP | | | ▼ | | | | | ▲ UF:SF | | UF: SF | ◄
Yu, 2022; a priori: DASH | ▲ | | ▲ | ▲ | Fr | LN | ▲ | | | | | ▼ RP | | | | ▲ | | ▼ | | | | | | ▼ Na^+^
Yu, 2022; a priori: DDG-15 | ▲ | | ▲ | ▲ | ▼ | ▲ | ▲ | | ▼ | ▲ | | ▼ R ▼ P | | | ▲ | | | ▼ | | ▲ | | ▼ | ▼ | ▼ Na^+^ | ▲ T
Zhang, 2023; a priori: EAT-LR | ▲ | ◄ | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼ | | ◄ | ◄ | | | ▼ | SB | ▲ | ◄ | ▼
Zhuang, 2021; a priori: DQs | ▲ | | | ▲ | | | ▲ | | ▼ | ▲ | | ▼ R ▼ P | | | ▲ | | | ▼ | | ▲ VO

* ▲Positively-scored component, reflecting higher intake within the food category as part of the pattern; ▼ Negatively-scored component, reflecting lower intake within the food category as part of the pattern; ◄ Neutral component, reflecting moderate (in contrast to higher or lower) intake within the food category as part of the pattern. Dietary pattern approaches included methods such as a priori index/score analysis (a priori), a posteriori latent class (LCA), principal component analysis (PCA), partial least squares regression (PLS), and reduced rank regression (RRR). The dietary pattern labels are abbreviated in this table due to limited space, but full details about each dietary pattern are described in Table 12.

† Abbreviations: AF, added fat; AP, animal products; AS, added sugar; C, coffee; ch, cheese; D, dairy/products; evo, extra-virgin olive oil; Fr, included with Fruits; F, included with Fish component; FS, included as Fish or Seafood; G, included with Grains/products; HF, high-fiber; L, included with Legumes; LCA, latent class analysis; LN, legumes and nuts; M, meat/ products; Na+, sodium; NP, not processed; NS, not sweetened; oo, olive oil; P, processed; PCA, principal component analysis; PLS, partial least square regression; pro, included with or as total, animal, or plant protein foods; RP, red and processed; RRR, reduced rank regression; rw, red wine; SB, sugar-sweetened beverage; SF, saturated fat; SO, sunflower oil; T, tea; Tr, Trans fat; UF, unsaturated; UF: SF, ratio of unsaturated-to-saturated fats; UP, ultra-processed; V, included with Vegetables; VO, vegetable oil; w, wine; W:R, white-to-red meat ratio; X, component excluded from pattern/analyses; y, yogurt