# Appendix 5 Excluded articles

The table below lists the 653 articles excluded after full-text screening for this systematic review question. At least one reason for exclusion is provided for each article, though this may not reflect all possible reasons. Information about articles excluded after title and abstract screening is available upon request.

The existing systematic evidence scan for this question in adults and older adults identified 72 articles for inclusion. After inclusion and exclusion criteria were established to update the review, the following 26 articles from the existing systematic review were excluded (rationale):

- Brunner EJ, Mosdol A, Witte DR, et al. Dietary patterns and 15-y risks of major coronary events, diabetes, and mortality. Am J Clin Nutr. 2008;87(5):1414–1421. doi:10.1093/ajcn/87.5.1414.(Data overlap)
- Casas R, Sacanella E, Urpi-Sarda M, et al. Long-term immunomodulatory effects of a Mediterranean diet in adults at high risk of cardiovascular disease in the PREvencion con DIeta MEDiterranea (PREDIMED) randomized controlled trial. J Nutr. 2016;146(9):1684–1693. doi:10.3945/jn.115.229476.(Data overlap)
- Casas R, Sacanella E, Urpi-Sarda M, et al. The effects of the Mediterranean diet on biomarkers of vascular wall inflammation and plaque vulnerability in subjects with high risk for cardiovascular disease. A randomized trial. PLoS One. 2014;9(6):e100084. doi:10.1371/journal.pone.0100084.(Data overlap)
- de Koning L. Low-carbohydrate diet scores and risk of type 2 diabetes in men. Am J Clin Nutr. 2011;93(4):844–850. doi:10.3945/ajcn.110.004333.(Intervention/Exposure/Comparator)
- Ericson U, Sonestedt E, Gullberg B, et al. High intakes of protein and processed meat associate with increased incidence of type 2 diabetes. Br J Nutr. 2013;109(6):1143–1153. doi:10.1017/s0007114512003017.(Intervention/Exposure/Comparator)
- Guasch-Ferre M, Becerra-Tomas N, Ruiz-Canela M, et al. Total and subtypes of dietary fat intake and risk of type 2 diabetes mellitus in the Prevencion con Dieta Mediterranea (PREDIMED) study. Am J Clin Nutr. 2017;105(3):723–735. doi:10.3945/ajcn.116.142034.(Intervention/Exposure/Comparator)
- Ha K, Joung H, Song Y. Inadequate fat or carbohydrate intake was associated with an increased incidence of type 2 diabetes mellitus in Korean adults: a 12-year community-based prospective cohort study. Diabetes Res Clin Pract. 2019;148:254–261. doi:10.1016/j.diabres.2019.01.024.(Intervention/Exposure/Comparator)
- Halton TL, Liu S, Manson JE, Hu FB. Low-carbohydrate-diet score and risk of type 2 diabetes in women. Am J Clin Nutr. 2008;87(2):339–346. doi:10.1093/ajcn/87.2.339.(Intervention/Exposure/Comparator)
- Kahleova H, Dort S, Holubkov R, Barnard ND. A plant-based high-carbohydrate, low-fat diet in overweight individuals in a 16-week randomized clinical trial: the role of carbohydrates. Nutrients. 2018;10(9). doi:10.3390/nu10091302.(Intervention/Exposure)
- Malik VS, Li Y, Tobias DK, Pan A, Hu FB. Dietary protein intake and risk of type 2 diabetes in US men and women. Am J Epidemiol. 2016;183(8):715–728. doi:10.1093/aje/kwv268.(Intervention/Exposure/Comparator)
- Nanri A, Mizoue T, Kurotani K, et al. Low-carbohydrate diet and type 2 diabetes risk in Japanese men and women: the Japan Public Health Center-Based Prospective Study. PLoS One. 2015;10(2):e0118377. doi:10.1371/journal.pone.0118377.(Intervention/Exposure/Comparator)
- Sakurai M, Nakamura K, Miura K, et al. Dietary carbohydrate intake, presence of obesity and the incident risk of type 2 diabetes in Japanese men. J Diabetes Investig. 2016;7(3):343–351. doi:10.1111/jdi.12433.(Intervention/Exposure/Comparator)
- Schulze MB, Schulz M, Heidemann C, Schienkiewitz A, Hoffmann K, Boeing H. Carbohydrate intake and incidence of type 2 diabetes in the European Prospective Investigation into Cancer and Nutrition (EPIC)-Potsdam Study. Br J Nutr. 2008;99(5):1107–1116. doi:10.1017/s0007114507853360.(Intervention/Exposure/Comparator)
- Shan R, Duan W, Liu L, et al. Low-carbohydrate, high-protein, high-fat diets rich in livestock, poultry and their products predict impending risk of type 2 diabetes in Chinese individuals that exceed their calculated caloric requirement. Nutrients. 2018;10(1). doi:10.3390/nu10010077.(Comparator)
- Shang X, Scott D, Hodge AM, et al. Dietary protein intake and risk of type 2 diabetes: results from the Melbourne Collaborative Cohort Study and a meta-analysis of prospective studies. Am J Clin Nutr. 2016;104(5):1352–1365. doi:10.3945/ajcn.116.140954.(Intervention/Exposure/Comparator)
- Simila ME, Kontto JP, Valsta LM, Mannisto S, Albanes D, Virtamo J. Carbohydrate substitution for fat or protein and risk of type 2 diabetes in male smokers. Eur J Clin Nutr. 2012;66(6):716–721. doi:10.1038/ejcn.2012.24.(Comparator)
- Sluijs I, Beulens JW, van der AD, Spijkerman AM, Grobbee DE, van der Schouw YT. Dietary intake of total, animal, and vegetable protein and risk of type 2 diabetes in the European Prospective Investigation into Cancer and Nutrition (EPIC)-NL study. Diabetes Care. 2010;33(1):43–48. doi:10.2337/dc09-1321.(Intervention/Exposure/Comparator)
- van Nielen M, Feskens EJ, Mensink M, et al. Dietary protein intake and incidence of type 2 diabetes in Europe: the EPIC-InterAct Case-Cohort Study. Diabetes Care. 2014;37(7):1854–1862. doi:10.2337/dc13-2627.(Comparator)
- Virtanen HEK, Koskinen TT, Voutilainen S, et al. Intake of different dietary proteins and risk of type 2 diabetes in men: the Kuopio Ischaemic Heart Disease Risk Factor Study. Br J Nutr. 2017;117(6):882–893. doi:10.1017/s0007114517000745.(Comparator was macronutrient distribution not dietary pattern)
- Johns DJ, Lindroos AK, Jebb SA, Sjostrom L, Carlsson LM, Ambrosini GL. Dietary patterns, cardiometabolic risk factors, and the incidence of cardiovascular disease in severe obesity. Obesity (Silver Spring). 2015;23(5):1063–1070. doi:10.1002/oby.20920.(Outcome, only intermediates from observational design)
- Konieczna J, Yanez A, Monino M, et al. Longitudinal changes in Mediterranean diet and transition between different obesity phenotypes. Clin Nutr. 2020;39(3):966–975. doi:10.1016/j.clnu.2019.04.002.(Outcome)
- Pinto X, Fanlo-Maresma M, Corbella E, et al. A Mediterranean diet rich in extra-virgin olive oil Is associated with a reduced prevalence of nonalcoholic fatty liver disease in older individuals at high cardiovascular risk. J Nutr. 2019;149(11):1920–1929. doi:10.1093/jn/nxz147.(Comparator)
- Poulsen SK, Due A, Jordy AB, et al. Health effect of the New Nordic Diet in adults with increased waist circumference: a 6-mo randomized controlled trial. Am J Clin Nutr. 2014;99(1):35–45. doi:10.3945/ajcn.113.069393.(Outcome, only intermediates from observational design)
- Salas-Salvado J, Bullo M, Babio N, et al. Reduction in the incidence of type 2 diabetes with the Mediterranean diet: results of the PREDIMED-Reus nutrition intervention randomized trial. Diabetes Care. 2011;34(1):14–19. doi:10.2337/dc10-1288.(Data overlap)
- Steffen LM, Van Horn L, Daviglus ML, et al. A modified Mediterranean diet score is associated with a lower risk of incident metabolic syndrome over 25 years among young adults: the CARDIA (Coronary Artery Risk Development in Young Adults) study. Br J Nutr. 2014;112(10):1654–1661. doi:10.1017/s0007114514002633.(Outcomes only intermediates from observational design)

Table A 8 List of excluded articles with rationale

No. | Citation | Rationale
1 | Abdrabalnabi AA, Rajaram S, Bitok E, et al. Effects of supplementing the usual diet with a daily dose of walnuts for two years on metabolic syndrome and its components in an elderly cohort. Journal: Article. Nutrients. 2020;12(2). doi:10.3390/nu12020451 | Intervention or Exposure
2 | Adam TC, Drummen M, Macdonald I, et al. Association of Psychobehavioral Variables With HOMA-IR and BMI Differs for Men and Women With Prediabetes in the PREVIEW Lifestyle Intervention. Diabetes care. 2021. doi:10.2337/dc21-0059 | Intervention or Exposure
3 | Aghaei N, Rouhani MH, Tabatabaei F, Larijani B, Azadbakht L. Effect of diverse low energy-dense versus healthy diet on metabolic outcomes in overweight/obese adolescents: A randomized controlled trial. Progress in Nutrition. 2019. 21:122-129. doi:10.23751/pn.v21i1-S.5721 | Study Duration
4 | Ahmad S, Moorthy MV, Demler OV, et al. Assessment of Risk Factors and Biomarkers Associated With Risk of Cardiovascular Disease Among Women Consuming a Mediterranean Diet. JAMA Netw Open. 2018 Dec 7;1(8):e185708. doi: 10.1001/jamanetworkopen.2018.5708. | Outcome
5 | Ainscough KM, O’Brien EC, Lindsay KL, et al. Nutrition, Behavior Change and Physical Activity Outcomes From the PEARS RCT-An mHealth-Supported, Lifestyle Intervention Among Pregnant Women With Overweight and Obesity. Front Endocrinol (Lausanne). 2019. 10:938. doi:10.3389/fendo.2019.00938. | Intervention or Exposure, Outcome
6 | Aittola K, Karhunen L, Männikkö R, et al. Enhanced Eating Competence Is Associated with Improved Diet Quality and Cardiometabolic Profile in Finnish Adults with Increased Risk of Type 2 Diabetes. Nutrients. 2021 Nov 11;13(11):4030. doi: 10.3390/nu13114030. | Intervention or Exposure
7 | Akpulat S, Gülsoy Kirnap N, Pfeiffer A. The effects of low-carbohydrate diet and protein-rich mixed diet on insulin sensitivity, basal metabolic rate and metabolic parameters in obese patients. Article. Turkish Journal of Endocrinology and Metabolism. 2020. 24:206213. doi:10.25179/tjem.2019-72200 | Intervention or Exposure, Comparator
8 | Al Aamri KS, Alrawahi AH, Al Busaidi N, et al. The effect of low-carbohydrate ketogenic diet in the management of obesity compared with low caloric, low-fat diet. Article in Press. Clinical Nutrition ESPEN. 2022 Jun;49:522-528. doi: 10.1016/j.clnesp.2022.02.110. | Intervention or Exposure
9 | Al Wattar B, Dodds J, Placzek A, et al. Mediterranean-style diet in pregnant women with metabolic risk factors (ESTEEM): A pragmatic multicentre randomised trial. Article. PLoS Medicine. 2019. 16. doi:10.1371/journal.pmed.1002857. | Data Overlap
10 | Alamolhoda SH, Simbar M, Mirmiran P, Mirabi P. The effectiveness of low trans-fatty acids dietary pattern in pregnancy and the risk of gestational diabetes mellitus. Article. Caspian Journal of Internal Medicine. 2019;10(2):197-204. doi:10.22088/cjim.10.2.197 | Intervention or Exposure
11 | Albert SL, Massar RE, Correa L, et al. Change in cardiometabolic risk factors in a pilot safety-net plant-based lifestyle medicine program. Front Nutr. Apr 20 2023;10doi:10.3389/fnut.2023.1155817 | Intervention or Exposure
12 | Al-Daghri NM, Amer OE, Hameidi A, et al. Effects of a 12-Month Hybrid (In-Person + Virtual) Education Program in the Glycemic Status of Arab Youth. Article. Nutrients. 2022;14(9)doi:10.3390/nu14091759 | Intervention or Exposure
13 | Aldubayan MA, Pigsborg K, Gormsen SMO, et al. A double-blinded, randomized, parallel intervention to evaluate biomarker-based nutrition plans for weight loss: The PREVENTOMICS study. Article. Clinical Nutrition. 2022;41(8):1834-1844. doi:10.1016/j.clnu.2022.06.032 | Intervention or Exposure, Study Duration
14 | Alfawaz H, Naeef AF, Wani K, et al. Improvements in Glycemic, Micronutrient, and Mineral Indices in Arab Adults with Pre-Diabetes Post-Lifestyle Modification Program. Nutrients. Nov 15 2019;11(11). doi:10.3390/nu11112775 | Intervention or Exposure
15 | Al-Hamdan. Identification of Education Models to Improve Health Outcomes in Arab Women with Pre-Diabetes. Nutrients. 2019;11(5):1113. Published 2019 May 18. doi:10.3390/nu11051113. | Intervention or Exposure
16 | Al-Hamdan. Efficacy of different prediabetes program models in improving clinical outcomes in people with prediabetes. Proceedings of the Nutrition Society. 2020;79(OCE2):E522. doi:10.1017/S0029665120004711. | Publication Status
17 | Aljefree NM, Almoraie NM, Shatwan IM. Association of two types of dietary pattern scores with cardiovascular disease risk factors and serum 25 hydroxy vitamin D levels in Saudi Arabia. Food Nutr Res. 2021;65. doi:10.29219/fnr.v65.5481 | Study Design
18 | Al-Salmi N, Cook P, souza MS. Diet Adherence among Adults with Type 2 Diabetes Mellitus: A Concept Analysis. Article. Oman Medical Journal. 2022;37(2)doi:10.5001/omj.2021.69 | Health Status
19 | Amer OE, Sabico S, Alfawaz HA, et al. Reversal of Prediabetes in Saudi Adults: results from an 18 Month Lifestyle Intervention. Journal Article; Randomized Controlled Trial. Nutrients. 2020;12(3). doi:10.3390/nu1203080 | Intervention or Exposure
20 | Amerikanou C, Kleftaki SA, Valsamidou E, Tzavara C, Gioxari A, Kaliora AC. Dietary Patterns, Cardiometabolic and Lifestyle Variables in Greeks with Obesity and Metabolic Disorders. Nutrients. Nov 28 2022;14(23)doi:10.3390/nu14235064 | Study Design
21 | Aminianfar A, Soltani S, Hajianfar H, Azadbakht L, Shahshahan Z, Esmaillzadeh A. The association between dietary glycemic index and load and risk of gestational diabetes mellitus: A prospective study. Diabetes Res Clin Pract. Dec 2020;170:108469. doi:10.1016/j.diabres.2020.108469 | Intervention or Exposure
22 | Anand C, Kranz RM, Husain S, et al. Bridging the gap between science and society: Long-term effects of the Healthy Lifestyle Community Programme (HLCP, cohort 1) on weight and the metabolic risk profile: A controlled study. Article in Press. BMJ Nutrition, Prevention and Health. 2022;doi:10.1136/bmjnph-2021-000340 | Intervention or Exposure
23 | Anand SS, Gupta M, Teo KK, et al. Causes and consequences of gestational diabetes in South Asians living in Canada: results from a prospective cohort study. Article. CMAJ open. 2017;5(3):E604-E611. doi:10.9778/cmajo.20170027 | Study Design
24 | Andersen E, van der Ploeg HP, van Mechelen W, et al. Contributions of changes in physical activity, sedentary time, diet and body weight to changes in cardiometabolic risk. International Journal of Behavioral Nutrition and Physical Activity. Dec 20 2021;18(1)doi:16610.1186/s12966-021-01237-1 | Intervention or Exposure, Outcome
25 | Antoni R, Johnston KL, Steele C, Carter D, Robertson MD, Capehorn MS. Efficacy of an intermittent energy restriction diet in a primary care setting. European Journal of Nutrition. 2020;59(6):2805-2812. doi:10.1007/s00394-019-02098-y | Intervention or Exposure
26 | Aqeel MM, Guo J, Lin L, et al. Temporal Dietary Patterns Are Associated with Obesity in US Adults. J Nutr. Dec 10 2020;150(12):3259-3268. doi:10.1093/jn/nxaa287 | Study Design
27 | Aridi YS, Walker JL, Roura E, Wright ORL. Adherence to the Mediterranean Diet and Chronic Disease in Australia: National Nutrition and Physical Activity Survey Analysis. Nutrients. Apr 28 2020;12(5). doi:10.3390/nu12051251 | Study Design
28 | Aro A, Kauppinen A, Kivinen N, et al. Life style intervention improves retinopathy status—the finnish diabetes prevention study. Article. Nutrients. 2019;11(7). doi:10.3390/nu11071691 | Intervention or Exposure, Outcome
29 | Asemi Z, Tabassi Z, Samimi M, Fahiminejad T, Esmaillzadeh A. Favourable effects of the Dietary Approaches to Stop Hypertension diet on glucose tolerance and lipid profiles in gestational diabetes: A randomised clinical trial. Brit J Nutr. 2013;109(11):2024-2030. doi:10.1017/S0007114512004242 | Health Status
30 | Asemi Z, Tabassi Z, Samimi M, Fahiminejad T, Esmaillzadeh A. Favorable effects of the Dietary Approaches to Stop Hypertension diet on glucose tolerance and lipid profiles in gestational diabetes: a randomised clinical trial - Expression of Concern. Br J Nutr. Aug 6 2021:1. doi:10.1017/S0007114521002002 | Study Design/Publica tion status
31 | Asghari G, Mirmiran P, Rezaeemanesh A, Mahdavi M, Azizi F, Hadaegh F. Changes in ideal cardiovascular health among Iranian adolescents: 2007-2008 to 2015-2017. Bmc Pediatrics. Jul 26 2022;22(1)doi:10.1186/s12887-022-03504-x | Study Design, Intervention or Exposure
32 | Assaf-Balut C, e la Torre NG, Durán A, et al. An early, universal mediterranean diet-based intervention in pregnancy reduces cardiovascular risk factors in the “fourth trimester”. Article. Journal of Clinical Medicine. 2019;8(9). doi:10.3390/jcm8091499 | Size of Study Groups. Data Overlap
33 | Assaf-Balut C, e la Torre NG, Fuentes M, et al. A high adherence to six food targets of the mediterranean diet in the late first trimester is associated with a reduction in the risk of materno-foetal outcomes: The st. carlos gestational diabetes mellitus prevention study. Article. Nutrients. 2019;11(1). doi:10.3390/nu11010066 | Intervention or Exposure, Data Overlap
34 | Assaf-Balut C, García De La Torre N, Duran A, et al. A mediterranean diet with an enhanced consumption of extra virgin olive oil and pistachios improves pregnancy outcomes in women without gestational diabetes mellitus: A sub-analysis of the St. Carlos gestational diabetes mellitus prevention study. Article. Annals of Nutrition and Metabolism. 2019;74(1):69-79. doi:10.1159/000495793 | Data Overlap
35 | Author NR. An investigation into the effect of a 12-week RCT comparing a low carbohydrate, high fat diet vs mainstream nutrition guidelines on metabolic health outcomes in overweight New Zealand Defence Force personnel. Trial registry record; Clinical trial protocol. http://wwwwhoint/trialsearch/Trial2aspx?TrialID=ACTRN12616001579482. 2016. | Publication Status
36 | Author N/A. Intervention with diet rich in two types of dietary fibre on glycemia, adipokines and lipid status in obese pre-diabetic subjects.Trial registry record; Clinical trial protocol. http://wwwwhoint/trialsearch/Trial2aspx?TrialID=ACTRN12613001118796. 2013. | Publication Status
37 | Author NR. MED Diet May Lower Diabetes Risk. Environmental Nutrition. 2021. 44:1-1. | Publication Status
38 | Azzini E, Peluso I, Intorre F, et al. Total and Plant Protein Consumption: The Role of Inflammation and Risk of Non-Communicable Disease. Article. International Journal of Molecular Sciences. 2022;23(14)doi:10.3390/ijms23148008 | Study Design, Intervention or Exposure
39 | Badr HE, Saunders T, Carter A, Reyes Castillo L, Bayoumy O, Barrett M. Impact of Lifestyle Modification on Quality of Life in Patients with Metabolic Syndrome: Findings from the CHANGE Program Intervention Study in Prince Edward Island, Canada. Metab Syndr Relat Disord. Nov 2022;20(9):532-542. doi:10.1089/met.2022.0056 | Outcome, Comparator
40 | Baleato CL, Ferguson JJA, Oldmeadow C, Mishra GD, Garg ML. Plant-Based Dietary Patterns versus Meat Consumption and Prevalence of Impaired Glucose Intolerance and Diabetes Mellitus: A Cross-Sectional Study in Australian Women. Nutrients. Oct 2022;14(19)doi:10.3390/nu14194152 | Study Design,
41 | Barabash A, Valerio JD, Garcia de la Torre N, et al. TCF7L2 rs7903146 polymorphism modulates the association between adherence to a Mediterranean diet and the risk of gestational diabetes mellitus. Metabol Open. Dec 2020;8:100069. doi:10.1159/000495793 | Data Overlap
42 | Barker K, Davy B. Is Consumption of Ultra-Processed Foods Associated with Cardiometabolic Risk? Scan’s Pulse. Winter2021 2021;41(1):1-5. | Publication Status
43 | Barnard ND, Rembert E, Freeman A, Bradshaw M, Holubkov R, Kahleova H. Blood Type Is Not Associated with Changes in Cardiometabolic Outcomes in Response to a Plant-Based Dietary Intervention. 121(6) | Intervention or Exposure, Comparator
44 | Barnard ND, Alwarith J, Rembert E, et al. A Mediterranean Diet and Low-Fat Vegan Diet to Improve Body Weight and Cardiometabolic Risk Factors: A Randomized, Cross-over Trial. J Am Coll Nutr. Feb 5 2021:1-13. doi:10.1080/07315724.2020.1869625 | Intervention or Exposure, Comparator
45 | Barrea L, Muscogiuri G, Pugliese G, e Alteriis G, Colao A, Savastano S. Metabolically healthy obesity (Mho) vs. metabolically unhealthy obesity (muo) phenotypes in pcos: Association with endocrine-metabolic profile, adherence to the mediterranean diet, and body composition. Article. Nutrients. 2021;13(11)doi:10.3390/nu13113925 | Outcome, Comparator
46 | Basu A, Feng D, Planinic P, Ebersole JL, Lyons TJ, Alexander JM. Dietary Blueberry and Soluble Fiber Supplementation Reduces Risk of Gestational Diabetes in Women with Obesity in a Randomized Controlled Trial. Article. The Journal of nutrition. 2021;151(5):1128-1138. doi:10.1093/jn/nxaa435 | Intervention or Exposure
47 | Basu A, Alman AC, Snell-Bergeon JK. Associations of Dietary Patterns and Nutrients with Glycated Hemoglobin in Participants with and without Type 1 Diabetes. Nutrients. Mar 23 2021;13(3).doi:10.3390/nu13031035 | Outcome
48 | Beasley JM, Yi SS, Ahn J, Kwon SC, Wylie-Rosett J. Dietary Patterns in Chinese Americans are Associated with Cardiovascular Disease Risk Factors, the Chinese American Cardiovascular Health Assessment (CHA CHA). Journal of Immigrant & Minority Health. 2019;21(5):1061-1069. doi:10.1007/s10903-018-0800-z | Study Design
49 | Becerra-Tomás N, Díaz-López A, Rosique-Esteban N, et al. Legume consumption is inversely associated with type 2 diabetes incidence in adults: A prospective assessment from the PREDIMED study. Article. Clinical Nutrition. 2018;37(3):906-913. doi:10.1016/j.clnu.2017.03.015 | Intervention or Exposure
50 | Beltaief K, Bouida W, Trabelsi I, et al. Metabolic effects of ramadan fasting in patients at high risk of cardiovascular diseases. Article. International Journal of General Medicine. 2019;12:247-254. doi:10.2147/IJGM.S172341 | Study Design, Intervention or Exposure
51 | Ben-Yacov O, Godneva A, Rein M, et al. Personalized Postprandial Glucose Response-Targeting Diet Versus Mediterranean Diet for Glycemic Control in Prediabetes. Diabetes Care. Sep 2021;44(9):1980-1991. doi:10.2337/dc21-0162 | Intervention or Exposure
52 | Bergia RE, Giacco R, Hjorth T, et al. Differential Glycemic Effects of Low-versus High-Glycemic Index Mediterranean-Style Eating Patterns in Adults at Risk for Type 2 Diabetes: The MEDGI-Carb Randomized Controlled Trial. Article. Nutrients. 2022;14(3)doi:10.3390/nu14030706 | Intervention or Exposure, Comparator
53 | Bhupathiraju SN, Sawicki CM, Goon S, et al. A healthy plant-based diet is favorably associated with cardiometabolic risk factors among participants of South Asian ancestry. American Journal of Clinical Nutrition. Oct 6 2022;116(4):1078-1090. doi:10.1093/ajcn/nqac174 | Size of Study Groups
54 | Bianco A, Franco I, Curci R, et al. Diet and Exercise Exert a Differential Effect on Glucose Metabolism Markers According to the Degree of NAFLD Severity. Nutrients. May 10 2023;15(10)doi:10.3390/nu15102252 | Health Status
55 | Blancas-Sánchez IM, Del Rosal Jurado M, Aparicio-Martínez P, et al. A Mediterranean-Diet-Based Nutritional Intervention for Children with Prediabetes in a Rural Town: A Pilot Randomized Controlled Trial. Nutrients. 2022;14(17)doi:10.3390/nu14173614 | Size of Study Groups
56 | Bogataj Jontez N, Kenig S, Sik Novak K, Petelin A, Jenko Praznikar Z, Mohorko N. Habitual low carbohydrate high fat diet compared with omnivorous, vegan, and vegetarian diets. Front Nutr. 2023;10:1106153. doi:10.3389/fnut.2023.1106153 | Study Design
57 | Bonaccio M, Di Castelnuovo A, Costanzo S, et al. Association of a traditional Mediterranean diet and non-Mediterranean dietary scores with all-cause and cause-specific mortality: prospective findings from the Moli-sani Study. Article. European Journal of Nutrition. 2021;60(2):729-746. doi:10.1007/s00394-020-02272-7 | Outcome
58 | Bonaccio M, Di Castelnuovo A, Costanzo S, et al. Impact of combined healthy lifestyle factors on survival in an adult general population and in high-risk groups: prospective results from the Moli-sani Study. Article. Journal of Internal Medicine. 2019;286(2):207-220. doi:10.1111/joim.12907 | Outcome, Comparator
59 | Borgen I, Smastuen MC, Jacobsen AF, et al. Effect of the Pregnant+ smartphone application in women with gestational diabetes mellitus: a randomised controlled trial in Norway. BMJ Open. Nov 11 2019;9(11):e030884. doi:10.1136/bmjopen-2019-030884 | Study Design, Intervention or Exposure
60 | Bozkuş Y, Mousa U, Demir CC, et al. Abdominal bioelectric impedance for follow-up of dieters: A prospective study. Article. Acta Endocrinologica. 2019;15(2):145-152. doi:10.4183/aeb.2019.145 | Study Design, Intervention or Exposure
61 | Brady EM, Gulsin GS, Mirkes EM, et al. Fibro-inflammatory recovery and type 2 diabetes remission following a low calorie diet but not exercise training: A secondary analysis of the DIASTOLIC randomised controlled trial. Diabetic Medicine. 2022;39(8):1-11. doi:10.1111/dme.14884 | Study Design, Intervention or Exposure, Health Status
62 | Brand C, Martins CML, Lemes VB, et al. Effects and prevalence of responders after a multicomponent intervention on cardiometabolic risk factors in children and adolescents with overweight/obesity: Action for health study. J Sports Sci. Mar 2020;38(6):682-691. doi:10.1080/02640414.2020.1725384 | Intervention or Exposure
63 | Brinkworth GD, Wycherley TP, Taylor PJ, Thompson CH. A Health Care Professional Delivered Low Carbohydrate Diet Program Reduces Body Weight, Haemoglobin A1c, Diabetes Medication Use and Cardiovascular Risk Markers—A Single-Arm Intervention Analysis. Article. Nutrients. 2022;14(20)doi:10.3390/nu14204406 | Study Design, Intervention or Exposure
64 | Broś-Konopielko M, Białek A, Oleszczuk-Modzelewska L, Zaleśkiewicz B, Różańska-Walędziak A, Czajkowski K. Nutritional, anthropometric and sociodemographic factors affecting fatty acids profile of pregnant women’s serum at labour—chemometric studies. Nutrients. 2021;13(9). doi:10.3390/nu13092948 | Intervention or Exposure, Outcome
65 | Buchman M, Jin Q, Sotos-Prieto M. The effectiveness of the Healthy Heart Score Intervention as a Primordial Prevention Tool in a Primary Care Setting: a Randomized Controlled Trial, Pilot Study. Journal: Conference Abstract. Revista espanola de nutricion humana y dietetica. 2019;23:204–205. | Publication Status
66 | Buckland G, Northstone K, Emmett PM, Taylor CM. The inflammatory potential of the diet in childhood is associated with cardiometabolic risk in adolescence/young adulthood in the ALSPAC birth cohort. Article. European Journal of Nutrition. 2022;61(7):3471-3486. doi:10.1007/s00394-022-02860-9 | Intervention or Exposure
67 | Bulunç NH, Yıldız E. The Relationship between Biochemical and Hemoglobin Results and Quality Index Scores of the Mediterranean Diet of Pregnant Women in the First and the Third Trimester. Article. Progress in Nutrition. 2021;23(4)doi:10.23751/pn.v23i4.11333 | Study Design
68 | Caferoglu Z, Erdal B, Hatipoglu N, Kurtoglu S. The effects of diet quality and dietary acid load on insulin resistance in overweight children and adolescents. Article in Press. Los efectos de la calidad de la dieta y la carga ácida de la dieta sobre la resistencia a la insulina en niños y adolescentes con sobrepeso. 2022;doi:10.1016/j.endinu.2021.07.008 | Study Design
69 | Cai J, Zhang Y, Nuli R, et al. Interaction between dietary patterns and TCF7L2 polymorphisms on type 2 diabetes mellitus among uyghur adults in Xinjiang province, China. Article. Diabetes, Metabolic Syndrome and Obesity: Targets and Therapy. 2019;12:239-255. doi:10.2147/DMSO.S191759 | Study Design
70 | Cai L, Yin J, Ma X, et al. Low-carbohydrate diets lead to greater weight loss and better glucose homeostasis than exercise: a randomized clinical trial. Article. Frontiers of medicine. 2021;15(3):460-471. doi:10.1007/s11684-021-0861-6 | Intervention or Exposure, Study Duration
71 | Cai Q, Dekker LH, Vinke PC, et al. Diet quality and incident chronic kidney disease in the general population: The Lifelines Cohort Study. Article. Clinical Nutrition. 2021;40(9):5099-5105. doi:10.1016/j.clnu.2021.07.033 | Outcome
72 | Calabrese FM, Disciglio V, Franco I, et al. A Low Glycemic Index Mediterranean Diet Combined with Aerobic Physical Activity Rearranges the Gut Microbiota Signature in NAFLD Patients. Nutrients. 2022;14(9)doi:10.3390/nu14091773 | Intervention or Exposure, Health Status
73 | Calvo-Malvar M, Benítez-Estévez AJ, Leis R, Sánchez-Castro J, Gude F. Changes in Dietary Patterns through a Nutritional Intervention with a Traditional Atlantic Diet: The Galiat Randomized Controlled Trial. Nutrients. 2021. 13:4233-4233. doi:10.3390/nu13124233 | Outcome
74 | Camargo A, Vals-Delgado C, Alcala-Diaz JF, et al. A Diet-Dependent Microbiota Profile Associated with Incident Type 2 Diabetes: From the CORDIOPREV Study. Mol Nutr Food Res. Oct 16 2020:e2000730. doi:10.1002/mnfr.202000730 | Intervention or Exposure
75 | Cani PD, Van Hul M. Do diet and microbes really ‘PREDICT’ cardiometabolic risks? Article. Nature Reviews Endocrinology. 2021;17(5):259-260. doi:10.1038/s41574-021-00480-7 | Study Design
76 | Cao Y, Chen C, Cui L, et al. A population-based survey for dietary patterns and prediabetes among 7555 Chinese adults in urban and rural areas in Jiangsu Province. Sci Rep. Jun 26 2020;10(1):10488. doi:10.1038/s41598-020-67028-z | Study Design
77 | Capurso A, Capurso C. The Mediterranean way: why elderly people should eat wholewheat sourdough bread—a little known component of the Mediterranean diet and healthy food for elderly adults. Aging Clinical & Experimental Research. 2020;32(1):1-5. doi:10.1007/s40520-019-01392-3 | Study Design, Publication Status
78 | Carballo-Casla A, Ortola R, Garcia-Esquinas E, et al. The Southern European Atlantic Diet and all-cause mortality in older adults. BMC Med. Feb 9 2021;19(1):36. doi:10.1186/s12916-021-01911-y | Outcome
79 | Carson AP, Long DL, Cherrington AL, et al. Sex Differences in Factors Contributing to the Racial Disparity in Diabetes Risk. Am J Prev Med. Apr 2021;60(4):e169-e177. doi:10.1016/j.amepre.2020.09.016 | Intervention or Exposure, Comparator
80 | Castro-Juarez AA, Serna-Gutiérrez A, Alemán-Mateo H, et al. Effectiveness of a Lifestyle Change Program on Insulin Resistance in Yaquis Indigenous Populations in Sonora, Mexico: PREVISY. Article. Nutrients. 2023;15(3)doi:10.3390/nu15030597 | Intervention or Exposure
81 | Ceraudo F, Caparello G, Galluccio A, et al. Impact of Mediterranean Diet Food Choices and Physical Activity on Serum Metabolic Profile in Healthy Adolescents: Findings from the DIMENU Project. Nutrients. Feb 19 2022;14(4)doi:10.3390/nu14040881 | Study Design, Intervention or Exposure
82 | Cha E, Pasquel FJ, Yan F, et al. Characteristics associated with early- vs. later-onset adult diabetes: The CARDIA study. Diabetes Res Clin Pract. Dec 2021;182:109144. doi:10.1016/j.diabres.2021.109144 | Size of Study Groups
83 | Chelu S, Bernad E, Craina M, et al. Prevalence of Gestational Diabetes in preCOVID-19 and COVID-19 Years and Its Impact on Pregnancy: A 5-Year Retrospective Study. Article. Diagnostics. 2022;12(5)doi:10.3390/diagnostics12051241 | Intervention or Exposure
84 | Chen B, Zeng J, Qin M, et al. The Association Between Plant-Based Diet Indices and Obesity and Metabolic Diseases in Chinese Adults: Longitudinal Analyses From the China Health and Nutrition Survey. 9 | Country
85 | Chen GC, Chai JC, Xing J, et al. Healthful eating patterns, serum metabolite profile and risk of diabetes in a population-based prospective study of US Hispanics/Latinos. Diabetologia. Jul 2022;65(7):1133-1144. doi:10.1007/s00125-022-05690-w | Intervention or Exposure, Comparator
86 | Chen Y, Qin Y, Zhang Z, et al. Association of the low-carbohydrate dietary pattern with postpartum weight retention in women. Food Funct. Nov 1 2021;12(21):10764-10772. doi:10.1039/d1fo00935d | Intervention or Exposure
87 | Chen Z, Qian F, Liu G, et al. Prepregnancy plant-based diets and the risk of gestational diabetes mellitus: a prospective cohort study of 14,926 women. Am J Clin Nutr. Dec 1 2021;114(6):1997-2005. doi:10.1093/ajcn/nqab275 | Life Stage
88 | Chen Q, Chen Y, Wu W, et al. Low-carbohydrate diet and maternal glucose metabolism in Chinese pregnant women. Br J Nutr. Aug 14 2021;126(3):392-400. | Intervention or Exposure, Outcome
89 | Chen Q, Feng Y, Yang H, et al. A vitamin pattern diet is associated with decreased risk of gestational diabetes mellitus in Chinese women: Results from a case control study in Taiyuan, China. Article. Journal of Diabetes Research. 2019;2019 | Study Design
90 | Chen Q, Wu W, Yang H, et al. A Vegetable Dietary Pattern Is Associated with Lowered Risk of Gestational Diabetes Mellitus in Chinese Women. Diabetes Metab J. Dec 2020;44(6):887-896. | Study Design
91 | Chen X, Su H, Kunii D, et al. The Effects of Mobile-App-Based Low-Carbohydrate Dietary Guidance on Postprandial Hyperglycemia in Adults with Prediabetes. Article. Diabetes Therapy. 2020;11(10):2341-2355. | Intervention or Exposure
92 | Chen Y, Zhou T, Sun D, et al. Distinct genetic subtypes of adiposity and glycemic changes in response to weight-loss diet intervention: the POUNDS Lost trial. Article. European Journal of Nutrition. 2021;60(1):249-258. | Intervention or Exposure
93 | Chen Z, Franco OH, Lamballais S, et al. Associations of specific dietary protein with longitudinal insulin resistance, prediabetes and type 2 diabetes: The Rotterdam Study. Clinical Nutrition. 2020;39(1):242-249. | Intervention or Exposure
94 | Chen Z, Qian F, Liu G, et al. 189-OR: Prepregnancy Plant-Based Diet and the Risk of Gestational Diabetes Mellitus: A Prospective Cohort Study of 15,999 Women. Diabetes. 2020;69:N.PAG-N.PAG. | Study Design, Publication Status
95 | Chevli PA, Mehta A, Allison M, et al. Relationship of American Heart Association’s Life Simple 7, Ectopic Fat, and Insulin Resistance in 5 Racial/Ethnic Groups. Article. Journal of Clinical Endocrinology and Metabolism. 2022;107(6):E2394-E2404. doi:10.1210/clinem/dgac102 | Study Design, Intervention or Exposure
96 | Choi BG, Dhawan T, Metzger K, et al. Image-Based Mobile System for Dietary Management in an American Cardiology Population: pilot Randomized Controlled Trial to Assess the Efficacy of Dietary Coaching Delivered via a Smartphone App Versus Traditional Counseling. Journal Article; Randomized Controlled Trial; Research Support, Non–U.S. Gov’t. JMIR mhealth and uhealth. 2019;7(4):e10755. doi:10.2196/10755 | Intervention or Exposure, Comparator
97 | Choudhary P, Ronkainen J, Nedelec R, et al. The relationship of life-course patterns of adiposity with type 2 diabetes, depression, and their comorbidity in the Northern Finland Birth Cohort 1966. Article in Press. International journal of obesity (2005). 2022;doi:10.1038/s41366-022-01134-y | Intervention or Exposure
98 | Christensen L, Thorning TK, Fabre O, Legrand R, Astrup A, Hjorth MF. Metabolic improvements during weight loss: The RNPC® cohort. Article. Obesity Medicine. 2019;14. doi:10.1016/j.obmed.2019.100085 | Study Design
99 | Chung S, Kim MS, Kwock CK. Dietary patterns may be nonproportional hazards for the incidence of type 2 diabetes: Evidence from Korean adult females. Article. Nutrients. 2019;11(10). doi:10.3390/nu11102522 | Comparator
100 | Cipryan L, Litschmannova M, Maffetone PB, et al. Very Low-Carbohydrate High-Fat Diet Improves Risk Markers for Cardiometabolic Health More Than Exercise in Men and Women With Overfat Constitution: Secondary Analysis of a Randomized Controlled Clinical Trial. Front Nutr. May 23 2022;9doi:10.3389/fnut.2022.867690 | Intervention or Exposure
101 | Cipryan L, Dostal T, Plews DJ, Hofmann P, Laursen PB. Adiponectin/leptin ratio increases after a 12-week very low-carbohydrate, high-fat diet, and exercise training in healthy individuals: A non-randomized, parallel design study. Nutr Res. Mar 2021;87:22-30. doi:10.1016/j.nutres.2020.12.012 | Intervention or Exposure
102 | Clemente G, Giorgini M, Della Pia N, et al. Effectiveness on major cardiovascular risk factors of an educational program to promote a Mediterranean type of diet among the employees of the company FCA Italia S.p.A. Diabetes Res Clin Pract. Sep 2021;179:109009. doi:10.1016/j.diabres.2021.109009 | Intervention or Exposure, Comparator
103 | Cobos-Palacios L, Ruiz-Moreno MI, Vilches-Perez A, et al. Metabolically healthy obesity: Inflammatory biomarkers and adipokines in elderly population. PLoS One. 2022;17(6):e0265362. doi:10.1371/journal.pone.0265362 | Intervention or Exposure, Comparator
104 | Cockerham WC, Bauldry S, Sims M. Obesity-Related Health Lifestyles of Late-Middle Age Black Americans: The Jackson Heart Study. Am J Prev Med. Jul 2022;63(1 Suppl 1):S47-S55. doi:10.1016/j.amepre.2022.02.014 | Study Design, Intervention or Exposure
105 | Cockroft MC, Bartlett TR, Wallace DC. Sleep, Nutrition, Disordered Eating, Problematic Tobacco and Alcohol Use, and Exercise in College Students With and Without Diabetes. Journal of Psychosocial Nursing & Mental Health Services. 2019;57(12):23-32. doi:10.3928/02793695-20190919-04 | Study Design, Intervention or Exposure
106 | Comas Rovira M, Moreno Baro A, Burgaya Guiu N, et al. The influence of obesity and diet quality on fetal growth and perinatal outcome. Nutr Hosp. Dec 20 2022;39(6):1205-1211. Influencia de la obesidad y la calidad de la dieta en el crecimiento fetal y resultados perinatales. doi:10.20960/nh.04076 | Confounders
107 | Corsi Decenti E, Zambri F, Salvatore MA, et al. Dietary habits, lifestyle, and gestational diabetes in immigrant women: a survey in Northwestern Tuscany (Central Italy). Epidemiol Prev. Jul-Aug 2022;46(4):259-267. Abitudini alimentari, stile di vita e diabete gestazionale nelle donne migranti. Un’indagine in Toscana Nord-Ovest. doi:10.19191/EP22.4.A372.074 | Study Design, Comparator
108 | Costa-Urrutia P, Alvarez-Farina R, Abud C, et al. Effect of multi-component school-based program on body mass index, cardiovascular and diabetes risks in a multi-ethnic study. BMC Pediatr. Nov 4 2019;19(1):401. doi:10.1186/s12887-019-1787-x | Intervention or Exposure
109 | Costello E, Goodrich J, Patterson WB, et al. Diet Quality Is Associated with Glucose Regulation in a Cohort of Young Adults. Nutrients. Sep 2022;14(18)doi:10.3390/nu14183734 | Size of Study Groups
110 | Courten BD, Karim MN, Hodge A. 714-P: Dietary Pattern and Risk of Type 2 Diabetes In Melbourne Collaborative Cohort. Diabetes. 2020;69:N.PAG-N.PAG. doi:10.2337/db20-714-P | Publication Status
111 | Crimarco A, Springfield S, Petlura C, et al. A randomized crossover trial on the effect of plant-based compared with animal-based meat on trimethylamine-N-oxide and cardiovascular disease risk factors in generally healthy adults: Study With Appetizing Plantfood-Meat Eating Alternative Trial (SWAP-MEAT). Am J Clin Nutr. Nov 11 2020;112(5):1188-1199. doi:10.1093/ajcn/nqaa203 | Intervention or Exposure,Stud y Duration
112 | Croxford S, Gupta D, Bandyopadhyay M, Itsiopoulos C. An evaluation of dietary intakes of a selected group of South Asian migrant women with gestational diabetes mellitus. Ethn Health. May 2021;26(4):487-503. | Study Design, Outcome
113 | Cuesta M, Fuentes M, Rubio M, et al. Incidence and regression of metabolic syndrome in a representative sample of the Spanish population: results of the cohort di@bet.es study. BMJ Open Diabetes Res Care. Oct 2020;8(1) | Outcome
114 | Curci R, Bianco A, Franco I, et al. The Effect of Low Glycemic Index Mediterranean Diet and Combined Exercise Program on Metabolic-Associated Fatty Liver Disease: A Joint Modeling Approach. J Clin Med. Jul 26 2022;11(15)doi:10.3390/jcm11154339 | Study Design, Intervention or Exposure
115 | Currenti W, Godos J, Alanazi AM, et al. Dietary Fats and Cardio-Metabolic Outcomes in a Cohort of Italian Adults. Article. Nutrients. 2022;14(20)doi:10.3390/nu14204294 | Study Design, Intervention or Exposure
116 | Cyr-Scully A, Howard AG, Sanzone E, et al. Characterizing the urban diet: development of an urbanized diet index. Nutr J. Sep 9 2022;21(1):55. doi:10.1186/s12937-022-00807-8 | Study Design
117 | Czekajło A, Różańska D, Zatońska K, Szuba A, Regulska-Ilow B. Association between dietary patterns and metabolic syndrome in the selected population of Polish adults-results of the PURE Poland Study. Article. European journal of public health. 2019;29(2):335-340. doi:10.1093/eurpub/cky207 | Study Design
118 | Czekajlo-Kozlowska A, Rozanska D, Zatonska K, Szuba A, Regulska-Ilow B. Association between egg consumption and elevated fasting glucose prevalence in relation to dietary patterns in selected group of Polish adults. Nutr J. Dec 30 2019;18(1):90. doi:10.1186/s12937-019-0516-5 | Intervention or Exposure, Outcome
119 | Das SK, Bukhari AS, Taetzsch AG, et al. Randomized trial of a novel lifestyle intervention compared with the Diabetes Prevention Program for weight loss in adult dependents of military service members. Am J Clin Nutr. 2021;114(4):1546-1559. doi:10.1093/ajcn/nqab259 | Intervention or Exposure
120 | De Giuseppe R, Bocchi M, Maffoni S, et al. Mediterranean diet and lifestyle habits during pregnancy: Is there an association with small for gestational age infants? an italian single centre experience. Nutrients. 2021;13(6)doi:10.3390/nu13061941 | Study Design, Outcome
121 | De La Torre NG, Assaf-Balut C, Varas IJ, et al. Effectiveness of following mediterranean diet recommendations in the real world in the incidence of gestational diabetes mellitus (Gdm) and adverse maternal-foetal outcomes: A prospective, universal, interventional study with a single group. the st carlos study. Nutrients. 2019;11(6) | Study Design
122 | de Luis D, Izaola O, Primo D. APOA-5 Genetic Variant rs662799: Role in Lipid Changes and Insulin Resistance after a Mediterranean Diet in Caucasian Obese Subjects. Dis Markers. 2021;2021:1257145. doi:10.1155/2021/1257145 | Intervention or Exposure, Comparator
123 | de Luis DA, Izaola O, Primo D, Aller R. Dietary-fat effect of the rs10830963 polymorphism in MTNR1B on insulin resistance in response to 3 months weight-loss diets. Endocrinol Diabetes Nutr (Engl Ed). Jan 2020;67(1):43-52. Efecto del polimorfismo rs10830963 MTNR1B y la composicion de grasa de la dieta en la resistencia a la insulina tras la perdida de peso durante 3 meses. doi:10.1016/j.endinu.2019.02.007 | Intervention or Exposure
124 | de Luis DA, Izaola O, Primo D, Aller R. Different effects of high-protein/low-carbohydrate versus standard hypocaloric diet on insulin resistance and lipid profile: Role of rs16147 variant of neuropeptide Y.Diabetes Research and Clinical Practice. 2019;156. doi:10.1016/j.diabres.2019.107825 | Intervention or Exposure, Comparator
125 | de Luis DA, Izaola O, Primo D, et al. Role of rs1501299 variant in the adiponectin gene on total adiponectin levels, insulin resistance and weight loss after a Mediterranean hypocaloric diet. Diabetes Research and Clinical Practice. 2019;148:262-267. doi:10.1016/j.diabres.2017.11.007 | Study Design, Intervention or Exposure
126 | de Luis DA, Primo D, Izaola O, Aller R. Adiponectin Gene Variant rs266729 Interacts with Different Macronutrient Distribution of Two Different Hypocaloric Diets. Lifestyle Genom. 2020;13(1):20-27. doi:10.1159/000503863 | Intervention or Exposure
127 | de Luis DA, Primo D, Izaola O, et al. Role of the variant in adiponectin gene rs266729 on weight loss and cardiovascular risk factors after a hypocaloric diet with the Mediterranean pattern. Nutrition. 2019;60:1-5. doi:10.1016/j.nut.2018.08.018 | Study Design, Intervention or Exposure
128 | de Luis DA, Primo D, Izaola O, Gomez E, Bachiller R. Serum Lipid and Adiponectin Improvements after a Mediterranean Dietary Pattern in Non-G-Allele Carriers of the Variant rs3774261. Lifestyle Genom. 2020;13(6):164-171. doi:10.1159/000508819 | Study Design, Intervention or Exposure
129 | De Pergola G, Zupo R, Lampignano L, et al. Higher Body Mass Index, Uric Acid Levels, and Lower Cholesterol Levels are Associated with Greater Weight Loss. Endocr Metab Immune Disord Drug Targets. 2020;20(8):1268-1281. doi:10.2174/1871530320666200429235830 | Study Design, Intervention or Exposure
130 | Deledda A, Palmas V, Heidrich V, et al. Dynamics of Gut Microbiota and Clinical Variables after Ketogenic and Mediterranean Diets in Drug-Naive Patients with Type 2 Diabetes Mellitus and Obesity. Metabolites. Nov 2022;12(11)doi:10.3390/metabo12111092 | Health Status
131 | Deng X, Niu W. Plant-Based Dietary Patterns and Incidence of Type 2 Diabetes. 2019;179:1603-1604. doi:10.1001/jamainternmed.2019.4860 | Study Design, Publication Status
132 | Desormeaux G, Petrick HL, Brunetta H, Holloway G. 1805-P: Dietary Nitrate Prevents High-Fat Diet-Induced Glucose Intolerance and Liver-Specific Reactive Oxygen Species Emission. Diabetes. 2020;69. doi:10.2337/db20-1805-P | Publication Status
133 | di Giuseppe R, Plachta-Danielzik S, Koch M, et al. Dietary pattern associated with selenoprotein P and MRI-derived body fat volumes, liver signal intensity, and metabolic disorders. Eur J Nutr. 2019;58(3):1067-1079. doi:10.1007/s00394-018-1624-2 | Study Design
134 | Dodd JM, Deussen AR, Louise J. A Randomised Trial to Optimise Gestational Weight Gain and Improve Maternal and Infant Health Outcomes through Antenatal Dietary, Lifestyle and Exercise Advice: The OPTIMISE Randomised Trial. Nutrients. Dec 2 2019;11(12). doi:10.3390/nu11122911 | Intervention or Exposure
135 | Domínguez-Coello S, Carrillo-Fernández L, Gobierno-Hernández J, et al. Decreased Consumption of Added Fructose Reduces Waist Circumference and Blood Glucose Concentration in Patients with Overweight and Obesity. The DISFRUTE Study: A Randomised Trial in Primary Care. Nutrients. 2020;12(4):1149-1149. doi:10.3390/nu12041149 | Intervention or Exposure
136 | Dong H, Sun H, Cai C, et al. A low-carbohydrate dietary pattern characterised by high animal fat and protein during the first trimester is associated with an increased risk of gestational diabetes mellitus in Chinese women: a prospective cohort study. Br J Nutr. Feb 18 2021:1-9. doi:10.1017/S0007114521000611 | Intervention or Exposure
137 | Dorans KS, Bazzano LA, Qi L, et al. Effects of a Low-Carbohydrate Dietary Intervention on Hemoglobin A1c: A Randomized Clinical Trial. JAMA Netw Open. Oct 3 2022;5(10):e2238645. doi:10.1001/jamanetworkopen.2022.38645 | Intervention or Exposure
138 | Dorenbos E, Drummen M, Adam T, et al. Effect of a high protein/low glycaemic index diet on insulin resistance in adolescents with overweight/obesity-A PREVIEW randomized clinical trial. Pediatr Obes. Jan 2021;16(1):e12702. doi:10.1111/ijpo.12702 | Intervention or Exposure, Comparator
139 | Drummen M, Adam TC, Macdonald IA, et al. Associations of changes in reported and estimated protein and energy intake with changes in insulin resistance, glycated hemoglobin, and BMI during the PREVIEW lifestyle intervention study. Am J Clin Nutr. Aug 10 2021. doi:10.1093/ajcn/nqab247 | Intervention or Exposure, Comparator
140 | Du M, Liu J, Han N, Zhao Z, Luo S, Wang H. Association between sleep duration in early pregnancy and risk of gestational diabetes mellitus: a prospective cohort study. Diabetes Metab. Dec 16 2020;47(5):101217. doi:10.1016/j.diabet.2020.101217 | Intervention or Exposure
141 | Ebbeling CB, Knapp A, Johnson A, et al. Effects of a low-carbohydrate diet on insulin-resistant dyslipoproteinemia-a randomized controlled feeding trial. Article in Press. Am J Clin Nutr. 2021;doi:10.1093/ajcn/nqab287 | Intervention or Exposure
142 | Effoe VS, Carnethon MR, Echouffo-Tcheugui JB, et al. The American Heart Association Ideal Cardiovascular Health and Incident Type 2 Diabetes Mellitus Among Blacks: The Jackson Heart Study. J Am Heart Assoc. 2017;6(6)doi:10.1161/JAHA.116.005008 | Intervention or Exposure, Comparator, Outcome
143 | Efthymiou V, Charmandari E, Vlachakis D, et al. Adolescent Self-Efficacy for Diet and Exercise Following a School-Based Multicomponent Lifestyle Intervention. Nutrients. 2022;14(1):97. doi:10.3390/nu14010097 | Intervention or Exposure, Outcome, Comparator
144 | Ekuni D, Furuta M, Kimura T, et al. Association between intensive health guidance focusing on eating quickly and metabolic syndrome in Japanese middle-aged citizens. Eat Weight Disord. Feb 2020;25(1):91-98. | Intervention or Exposure
145 | Epel E, Laraia B, Coleman-Phox K, et al. Effects of a Mindfulness-Based Intervention on Distress, Weight Gain, and Glucose Control for Pregnant Low-Income Women: A Quasi-Experimental Trial Using the ORBIT Model. Article. International journal of behavioral medicine. 2019;26(5):461-473. | Intervention or Exposure
146 | Esfandiar Z, Hosseini-Esfahani F, Mirmiran P, Azizi F. The association of dietary macronutrients composition with the incidence of type 2 diabetes, using iso-energetic substitution models: Tehran Lipid and Glucose Study. Prim Care Diabetes. Dec 2021;15(6):1080-1085. doi:10.1016/j.pcd.2021.09.006 | Intervention or Exposure
147 | Esfandiar Z, Hosseini-Esfahani F, Mirmiran P, Yuzbashian E, Azizi F. The Association of Dietary Polyphenol Intake with the Risk of Type 2 Diabetes: Tehran Lipid and Glucose Study. Diabetes Metab Syndr Obes. 2020;13:1643-1652. | Intervention or Exposure
148 | Eshak ES, Iso H, Muraki I, Tamakoshi A. Among the water-soluble vitamins, dietary intakes of vitamins C, B2 and folate are associated with the reduced risk of diabetes in Japanese women but not men. Article. British Journal of Nutrition. 2019;121(12):1357-1364. | Intervention or Exposure
149 | Fagherazzi S, Farias DR, Belfort GP, et al. The impact of the DASH diet on glycaemic control and consumption of processed and ultra-processed foods in pregnant women with pre-gestational diabetes mellitus: a randomized clinical trial. Journal: Article in Press. British journal of nutrition. 2020; | Health Status
150 | Fagherazzi S, Farias DR, Belfort GP, et al. Impact of the Dietary Approaches to Stop Hypertension (DASH) diet on glycaemic control and consumption of processed and ultraprocessed foods in pregnant women with pre-gestational diabetes mellitus: a randomised clinical trial. Br J Nutr. Sep 28 2021;126(6):865-876. | Health Status
151 | Falkenhain K, Locke SR, Lowe DA, et al. Keyto app and device versus WW app on weight loss and metabolic risk in adults with overweight or obesity: A randomized trial. Article in Press. Obesity. 2021;doi:10.1002/oby.23242 | Intervention or Exposure
152 | Farabi SS, Smith GI, Schweitzer GG, Stein RI, Klein S. Do lifestyle factors and quality of life differ in people with metabolically healthy and unhealthy obesity? | Study Design,
153 | Farhadnejad H, Teymoori F, Asghari G, Mokhtari E, Mirmiran P, Azizi F. The higher adherence to a healthy lifestyle score is associated with a decreased risk of type 2 diabetes in Iranian adults. Bmc Endocrine Disorders. Feb 17 2022;22(1). doi:10.1186/s12902-022-00961-4 | Intervention or Exposure
154 | Farpour-Lambert NJ, Martin XE, Bucher Della Torre S, et al. Effectiveness of individual and group programmes to treat obesity and reduce cardiovascular disease risk factors in pre-pubertal children. Clin Obes. Dec 2019;9(6):e12335. | Intervention or Exposure
155 | Feng Q, Yang M, Dong H, et al. Dietary fat quantity and quality in early pregnancy and risk of gestational diabetes mellitus in Chinese women: a prospective cohort study. Br J Nutr. Aug 1 2022:1-10. doi:10.1017/S0007114522002422 | Intervention or Exposure
156 | Fernandez CA, Potts K, Bazzano LA. Effect of ideal protein versus low-fat diet for weight loss: A randomized controlled trial. Article in Press. Obesity Science and Practice. 2021;doi:10.1002/osp4.567 | Intervention or Exposure
157 | Fernández-García JC, Martínez-Sánchez MA, Bernal-López MR, et al. Effect of a lifestyle intervention program with energy-restricted Mediterranean diet and exercise on the serum polyamine metabolome in individuals at high cardiovascular disease risk: A randomized clinical trial. Article. American Journal of Clinical Nutrition. 2020;111(5):975-982. doi:10.1093/ajcn/nqaa064 | Comparator
158 | Fernandez-Lazaro CI, Sayon-Orea C, Toledo E, Moreno-Iribas C, Guembe MJ, Investigators RS. Association of ideal cardiovascular health with cardiovascular events and risk advancement periods in a Mediterranean population-based cohort. BMC Med. Jul 5 2022;20(1):232. doi:10.1186/s12916-022-02417-x | Outcome
159 | Fernandez-Lazaro CI, Toledo E, Salas-Salvado J, et al. PREDIMED-Plus trial: one-year changes in the quality of dietary carbohydrate intake and concurrent changes in cardiovascular risk factors. Journal: Conference Abstract. Annals of nutrition & metabolism. 2019;75:20–21. | Publication Status
160 | Fernández-Ruiz VE, Solé-Agustí M, Armero-Barranco D, Cauli O. Weight Loss and Improvement of Metabolic Alterations in Overweight and Obese Children Through the I2AO2 Family Program: A Randomized Controlled Clinical Trial. Biological Research For Nursing. 2021;23(3):488-503. doi:10.1177/1099800420987303 | Intervention or Exposure
161 | Flores AC, Heron C, Kim JI, et al. Prospective Study of Plant-Based Dietary Patterns and Diabetes in Puerto Rican Adults. J Nutr. Dec 3 2021;151(12):3795-3800. doi:10.1093/jn/nxab301 | Size of Study Groups
162 | Ford CN, Weber MB, Staimez LR, et al. Dietary changes in a diabetes prevention intervention among people with prediabetes: the Diabetes Community Lifestyle Improvement Program trial. Article. Acta Diabetologica. 2019;56(2):197-209. | Intervention or Exposure
163 | Fu Y, Yang Y, Zhu L, Chen J, Yu N, Zhao M. Effect of dietary n-6: n-3 Poly-Unsaturated fatty acids ratio on gestational diabetes mellitus: a prospective cohort. Gynecol Endocrinol. Jul 2022;38(7):583-587. doi:10.1080/09513590.2022.2073995 | Intervention or Exposure
164 | Gabiola J, Morales D, Quizon O, et al. The EffectiveNess of LIfestyle with Diet and Physical Activity Education ProGram Among Prehypertensives and Stage 1 HyperTENsives in an Urban Community Setting (ENLIGHTEN) Study. J Community Health. Jun 2020;45(3):478-487. | Intervention or Exposure
165 | Gabriel Da Silva LB, Rosado EL, De Carvalho Padilha P, et al. Food intake of women with gestational diabetes mellitus, in accordance with two methods of dietary guidance: A randomised controlled clinical trial. Article. British Journal of Nutrition. 2019;121(1):82-92. | Intervention or Exposure, Health Status
166 | Gadgil MD, Ingram KH, Appiah D, et al. Prepregnancy Protein Source and BCAA Intake Are Associated with Gestational Diabetes Mellitus in the CARDIA Study. Int J Environ Res Public Health. Oct 29 2022;19(21)doi:10.3390/ijerph192114142 | Life Stage
167 | Gadgil MD, Kanaya AM, Sands C, et al. Diet Patterns Are Associated with Circulating Metabolites and Lipid Profiles of South Asians in the United States. Article. Journal of Nutrition. 2022;152(11):2358-2366. doi:10.1093/jn/nxac191 | Study Design, Outcome
168 | Gainfort A, Delahunt A, Killeen SL, et al. Energy-Adjusted Dietary Inflammatory Index in pregnancy and maternal cardiometabolic health: findings from the ROLO study. Article. AJOG Global Reports. 2023;3(2)doi:10.1016/j.xagr.2023.100214 | Intervention or Exposure
169 | Gajda R, Raczkowska E, Sobieszczańska M, Noculak Ł, Szymala-Pędzik M, Godyla-Jabłoński M. Diet Quality Variation among Polish Older Adults: Association with Selected Metabolic Diseases, Demographic Characteristics and Socioeconomic Status. Article in Press. International journal of environmental research and public health. 2023;20(4)doi:10.3390/ijerph20042878 | Study Design
170 | Garbutt J, England C, Jones AG, Andrews RC, Salway R, Johnson L. Is glycaemic control associated with dietary patterns independent of weight change in people newly diagnosed with type 2 diabetes? Prospective analysis of the Early-ACTivity-In-Diabetes trial. 20(1) | Health Status
171 | Garbutt JDW, England C, Jones AG, Andrews RC, Johnson L. Are changes in a low-carbohydrate, high-fat diet pattern associated with subsequent changes in HbA1c during an intensive diet and physical activity intervention? Journal: Conference Abstract. Diabetic medicine. 2020;37(SUPPL 1):44–. | Publication Status
172 | Gardner CD, Landry MJ, Perelman D, et al. Effect of a Ketogenic Diet versus Mediterranean Diet on HbA1c in Individuals with Prediabetes and Type 2 Diabetes Mellitus: the Interventional Keto-Med Randomized Crossover Trial. | Comparator
173 | Garnæs KK, Elvebakk T, Salvesen Ø, et al. Dietary intake in early pregnancy and glycemia in late pregnancy among women with obesity. Article. Nutrients. 2022;14(1)doi:10.3390/nu14010105 | Intervention or Exposure
174 | Garr Barry V, Stewart M, Soleymani T, Desmond RA, Goss AM, Gower BA. Greater Loss of Central Adiposity from Low-Carbohydrate versus Low-Fat Diet in Middle-Aged Adults with Overweight and Obesity. Nutrients. Jan 31 2021;13(2) | Intervention or Exposure
175 | Geiker NRW, Magkos F, Zingenberg H, et al. A high-protein low-glycemic index diet attenuates gestational weight gain in pregnant women with obesity: The “An optimized programming of healthy children” (APPROACH) randomized controlled trial. Article. American Journal of Clinical Nutrition. 2022;115(3):970-979. doi:10.1093/ajcn/nqab405 | Intervention or Exposure
176 | George ES, Georgousopoulou EN, Mellor DD, Chrysohoou C, Pitsavos C, Panagiotakos DB. Exploring the Path of Mediterranean Diet, Non-Alcoholic Fatty Liver Disease (NAFLD) and Inflammation towards 10-Year Cardiovascular Disease (CVD) Risk: The ATTICA Study 10-Year Follow-Up (2002–2012). Article. Nutrients. 2022;14(12)doi:10.3390/nu14122367 | Outcome
177 | Gepner Y, Shelef I, Komy O, et al. The beneficial effects of Mediterranean diet over low-fat diet may be mediated by decreasing hepatic fat content. Article. Journal of Hepatology. 2019;71(2):379-388. | Intervention or Exposure
178 | Gete DG, Waller M, Mishra GD. Prepregnancy dietary patterns and risk of preterm birth and low birth weight: Findings from the Australian Longitudinal Study on Women’s Health. Article. American Journal of Clinical Nutrition. 2020;111(5):1048-1058. | Outcome, Comparator
179 | Giacomello L, Bordignon S, Salm D, et al. RETRACTED: Effects of the application of a food processing-based classification system in obese women: A randomized controlled pilot study. Nutr Health. Feb 7 2023:2601060231153947. doi:10.1177/02601060231153947 | Intervention or Exposure
180 | Giardina S, Hernández-Alonso P, Díaz-López A, Salas-Huetos A, Salas-Salvadó J, Bulló M. Changes in circulating miRNAs in healthy overweight and obese subjects: Effect of diet composition and weight loss. Article. Clinical Nutrition. 2019;38(1):438-443. | Intervention or Exposure
181 | Gillingham MB, Elizondo G, Behrend A, et al. Higher dietary protein intake preserves lean body mass, lowers liver lipid deposition, and maintains metabolic control in participants with long-chain fatty acid oxidation disorders. Article. Journal of Inherited Metabolic Disease. 2019;42(5):857-869. | Intervention or Exposure, Health Status
182 | Giontella A, Bonafini S, Tagetti A, et al. Relation between dietary habits, physical activity, and anthropometric and vascular parameters in children attending the primary school in the Verona South District. Article. Nutrients. 2019;11(5) | Study Design
183 | Goff LM, Rivas C, Moore A, Beckley-Hoelscher N, Reid F, Harding S. Healthy Eating and Active Lifestyles for Diabetes (HEAL-D), a culturally tailored self-management education and support program for type 2 diabetes in black-British adults: a randomized controlled feasibility trial. BMJ Open Diabetes Res Care. Sep 2021;9(1)doi:10.1136/bmjdrc-2021-002438 | Intervention or Exposure, Health Status
184 | Goff LM, Huang P, Silva MJ, et al. Associations of dietary intake with cardiometabolic risk in a multi-ethnic cohort: A longitudinal analysis of the Determinants of Adolescence, now young Adults, Social well-being and Health (DASH) study. Article. British Journal of Nutrition. 2019;121(9):1069-1079. | Intervention or Exposure
185 | Goldenshluger A, Constantini K, Goldstein N, et al. Effect of Dietary Strategies on Respiratory Quotient and Its Association with Clinical Parameters and Organ Fat Loss: A Randomized Controlled Trial. Nutrients. Jun 29 2021;13(7) | Intervention or Exposure
186 | González CA, Bonet C, Pablo Md, et al. Greenhouse gases emissions from the diet and risk of death and chronic diseases in the EPIC-Spain cohort. European Journal of Public Health. 2021;31(1):130-135. | Intervention or Exposure
187 | González-Domínguez Á, Domínguez-Riscart J, Millán-Martínez M, Lechuga-Sancho AM, González-Domínguez R. Exploring the association between circulating trace elements, metabolic risk factors, and the adherence to a Mediterranean diet among children and adolescents with obesity. 10 | Study Design
188 | Gower BA, Pearson K, Bush N, et al. Diet pattern may affect fasting insulin in a large sample of black and white adults. Article. European Journal of Clinical Nutrition. 2021;75(4):628-635. doi:10.1038/s41430-020-00762-9 | Outcome
189 | Grammatikopoulou MG, Nigdelis MP, Haidich AB, et al. Diet Quality and Nutritional Risk Based on the FIGO Nutrition Checklist among Greek Pregnant Women: A Cross-Sectional Routine Antenatal Care Study. Article. Nutrients. 2023;15(9)doi:10.3390/nu15092019 | Study Design
190 | Grangeiro É, Trigueiro MS, Siais LO, et al. Hypocaloric diet with lower meal frequency did not affect weight loss, body composition and insulin responsiveness, but improved lipid profile: a randomized clinical trial. Article. Food & function. 2021;12(24):12594-12605. doi:10.1039/d1fo00484k | Intervention or Exposure, Comparator
191 | Gray KL, Clifton PM, Keogh JB. The effect of intermittent energy restriction on weight loss and diabetes risk markers in women with a history of gestational diabetes: a 12-month randomized control trial. American Journal of Clinical Nutrition. 2021;114(2):794-803. | Intervention or Exposure, Comparator
192 | Gray ME, Bae S, Ramachandran R, et al. Dietary Patterns and Prevalent NAFLD at Year 25 from the Coronary Artery Risk Development in Young Adults (CARDIA) Study. Nutrients. Feb 2022;14(4)doi:10.3390/nu14040854 | Outcome
193 | Guasch-Ferre M, Santos JL, Martinez-Gonzalez MA, et al. Glycolysis/gluconeogenesis- and tricarboxylic acid cycle-related metabolites, Mediterranean diet, and type 2 diabetes. Am J Clin Nutr. Apr 1 2020;111(4):835-844. | Size of Study Groups
194 | Gunther J, Hoffmann J, Stecher L, et al. Associations between antenatal lifestyle and the risk for gestational diabetes mellitus in the GeliS trial-an exploratory secondary cohort analysis. Journal: Conference Abstract. Obesity facts. 2021;14(SUPPL 1):102–. | Publication Status
195 | Guo X, Liu S, Zeng X, et al. Dietary patterns and diabetes risk in Southern Chinese in Guangxi Zhuang autonomous region. Article. International Journal of Diabetes in Developing Countries. 2023;43(2):258-266. doi:10.1007/s13410-022-01077-0 | Study Design
196 | Gurdeniz G, Uusitupa M, Hermansen K, et al. Analysis of the SYSDIET Healthy Nordic Diet randomized trial based on metabolic profiling reveal beneficial effects on glucose metabolism and blood lipids. Clin Nutr. Feb 2022;41(2):441-451. doi:10.1016/j.clnu.2021.12.031 | Intervention or Exposure, Outcome
197 | Ha K, Joung H, Song Y. Inadequate fat or carbohydrate intake was associated with an increased incidence of type 2 diabetes mellitus in Korean adults: A 12-year community-based prospective cohort study. Article. Diabetes Research and Clinical Practice. 2019;148:254-261. | Intervention or Exposure
198 | Hailili G, Chen Z, Tian T, et al. Dietary patterns and their associations with the metabolic syndrome and predicted 10-year risk of CVD in northwest Chinese adults. British Journal of Nutrition. 2021;126(6):913-922. | Outcome
199 | Hall M, Walicka M, Panczyk M, Traczyk I. Assessing Long-Term Impact of Dietary Interventions on Occurrence of Symptoms Consistent with Hypoglycemia in Patients without Diabetes: A One-Year Follow-Up Study. Article. Nutrients. 2022;14(3)doi:10.3390/nu14030497 | Outcome
200 | Han L, Zhang T, You D, et al. Temporal and mediation relations of weight loss, and changes in insulin resistance and blood pressure in response to 2-year weight-loss diet interventions: the POUNDS Lost trial. Article. European Journal of Nutrition. 2022;61(1):269-275. doi:10.1007/s00394-021-02643-8 | Intervention or Exposure
201 | Hao Y, Qu L, Guo Y, et al. Association of pre-pregnancy low-carbohydrate diet with maternal oral glucose tolerance test levels in gestational diabetes. BMC Pregnancy Childbirth. Sep 26 2022;22(1):734. doi:10.1186/s12884-022-05059-2 | Study Design, Intervention or Exposure
202 | Hardy DS, Racette SB, Garvin JT, Gebrekristos HT, Mersha TB. Ancestry specific associations of a genetic risk score, dietary patterns and metabolic syndrome: a longitudinal ARIC study. BMC Med Genomics. May 1 2021;14(1):118. doi:10.1186/s12920-021-00961-8 | Outcome
203 | Harper CA, Smythe K, Wong VW, Rollo ME, Collins CE. Comparison of pre-diagnosis dietary intake of women with gestational diabetes mellitus to dietary recommendations. Midwifery. Sep 2021;100:103032. | Study Design
204 | Harreiter J, Simmons D, Desoye G, et al. Nutritional lifestyle intervention in obese pregnant women, including lower carbohydrate intake, is associated with increased maternal free fatty acids, 3-b-hydroxybutyrate, and fasting glucose concentrations: A secondary factorial analysis of the European multicenter, randomized controlled DALI lifestyle intervention trial. Article. Diabetes Care. 2019;42(8):1380-1389. | Intervention or Exposure
205 | Hasbullah F, Mohd Yusof B, Appannah G, et al. Dietary Patterns and Type 2 Diabetes Risk in Malaysian Women With and Without History of Gestational Diabetes Mellitus. Journal of the Academy of Nutrition & Dietetics. 2021;121:A22-A22. | Publication Status
206 | Haywood CJ, Prendergast LA, Lim R, Lappas M, Lim WK, Proietto J. Obesity in older adults: Effect of degree of weight loss on cardiovascular markers and medications. Article. Clinical Obesity. 2019;9(4) | Intervention or Exposure
207 | He M, Wang J, Liang Q, et al. Time-restricted eating with or without low-carbohydrate diet reduces visceral fat and improves metabolic syndrome: A randomized trial. | Intervention or Exposure
208 | He Y, Fang Y, Bromage S, et al. Application of the Global Diet Quality Score in Chinese Adults to Evaluate the Double Burden of Nutrient Inadequacy and Metabolic Syndrome. J Nutr. Oct 23 2021;151(12 Suppl 2):93S-100S. doi:10.1093/jn/nxab162 | Study Design
209 | He YM, Chen WL, Kao TW, Wu LW, Yang HF, Peng TC. Relationship between Ideal Cardiovascular Health and Incident Proteinuria: A 5 Year Retrospective Cohort Study. Nutrients. Oct 2022;14(19)doi:10.3390/nu14194040 | Outcome, Country
210 | He D, Qiao Y, Xiong S, Liu S, Ke C, Shen Y. Association between Dietary Quality and Prediabetes based on the Diet Balance Index. Sci Rep. Feb 21 2020;10(1):3190. | Study Design, Country
211 | Hendryx M, Dinh P, Chow A, et al. Lifestyle and Psychosocial Patterns and Diabetes Incidence Among Women with and Without Obesity: a Prospective Latent Class Analysis. Prev Sci. Aug 2020;21(6):850-860. | Intervention or Exposure
212 | Henning SM, Yang J, Woo SL, et al. Hass Avocado Inclusion in a Weight-Loss Diet Supported Weight Loss and Altered Gut Microbiota: a 12-Week Randomized, Parallel-Controlled Trial. Journal: Article. Current developments in nutrition. 2019;3(8) | Intervention or Exposure
213 | Hermenegildo-López Y, Donat-Vargas C, Sandoval-Insausti H, et al. A Higher Intake of Energy at Dinner Is Associated with Incident Metabolic Syndrome: A Prospective Cohort Study in Older Adults. 13(9) | Intervention or Exposure
214 | Hernández-Alonso P, Giardina S, Cañueto D, Salas-Salvadó J, Cañellas N, Bulló M. Changes in Plasma Metabolite Concentrations after a Low-Glycemic Index Diet Intervention. Article. Molecular nutrition & food research. 2019;63(1):e1700975. | Intervention or Exposure
215 | Hernando-Redondo J, Toloba A, Benaiges D, et al. Mid- and long-term changes in satiety-related hormones, lipid and glucose metabolism, and inflammation after a Mediterranean diet intervention with the goal of losing weight: A randomized, clinical trial. Front Nutr. 2022;9:950900. doi:10.3389/fnut.2022.950900 | Intervention or Exposure
216 | Hinkle SN, Bao W, Wu J, et al. Association of Habitual Alcohol Consumption with Long-term Risk of Type 2 Diabetes among Women with a History of Gestational Diabetes. Article. JAMA Network Open. 2021;4(9)doi:10.1001/jamanetworkopen.2021.24669 | Intervention or Exposure
217 | Hjorth MF, Astrup A, Zohar Y, et al. Personalized nutrition: pretreatment glucose metabolism determines individual long-term weight loss responsiveness in individuals with obesity on low-carbohydrate versus low-fat diet. Article. International Journal of Obesity. 2019;43(10):2037-2044. | Intervention or Exposure
218 | Hjorth MF, Bray GA, Zohar Y, et al. Pretreatment fasting glucose and insulin as determinants of weight loss on diets varying in macronutrients and dietary fibers—The POUNDS LOST study. Article. Nutrients. 2019;11(3) | Intervention or Exposure
219 | Hjorth MF, Corella D, Astrup A, et al. High fat diets for weight loss among subjects with elevated fasting glucose levels: The PREDIMED study. Article. Obesity Medicine. 2020;18 | Intervention or Exposure, Comparator, Outcome
220 | Holder M, Kapellen T, Ziegler R, et al. Diagnosis, Therapy and Follow-Up of Diabetes Mellitus in Children and Adolescents. Article. Experimental and Clinical Endocrinology and Diabetes. 2022;130(6):S49-S79. doi:10.1055/a-1624-3388 | Study Design, Publication Status
221 | Hosseini-Esfahani F, Beheshti N, Koochakpoor G, Mirmiran P, Azizi F. Meat Food Group Intakes and the Risk of Type 2 Diabetes Incidence. Front Nutr. 2022;9:891111. doi:10.3389/fnut.2022.891111 | Intervention or Exposure
222 | Hosseinpour-Niazi S, Mirmiran P, Hadaegh F, et al. Improvement of glycemic indices by a hypocaloric legume-based DASH diet in adults with type 2 diabetes: a randomized controlled trial. Eur J Nutr. Sep 2022;61(6):3037-3049. doi:10.1007/s00394-022-02869-0 | Health Status
223 | Hrolfsdottir L, Gunnarsdottir I, Birgisdottir BE, et al. Can a simple dietary screening in early pregnancy identify dietary habits associated with gestational diabetes? Article. Nutrients. 2019;11(8) | Data Overlap
224 | Hu C, Mu Y, Wan Q, et al. Association between birth weight and diabetes: Role of body mass index and lifestyle in later life. J Diabetes. Jan 2020;12(1):10-20. | Intervention or Exposure
225 | Hu J, Oken E, Aris IM, et al. Dietary patterns during pregnancy are associated with the risk of gestational diabetes mellitus: Evidence from a chinese prospective birth cohort study. Article. Nutrients. 2019;11(2) | Data Overlap
226 | Hua Y, Zhang Z, Liu A. Long-Term Diet Quality and Risk of Diabetes in a National Survey of Chinese Adults. Nutrients. Nov 16 2022;14(22)doi:10.3390/nu14224841 | Outcome
227 | Huang L, Shang L, Yang W, et al. High starchy food intake may increase the risk of adverse pregnancy outcomes: a nested casecontrol study in the Shaanxi province of Northwestern China. BMC Pregnancy Childbirth. Oct 21 2019;19(1):362. | Outcome
228 | Huo YT, Cao SX, Liu JC, et al. The Association between Plant-Based Diet Indices and Metabolic Syndrome in Chinese Adults: Longitudinal Analyses from the China Health and Nutrition Survey. Nutrients. Mar 2023;15(6)doi:10.3390/nu15061341 | Outcome
229 | Iglesies-Grau J, Dionne V, Bherer L, et al. Metabolic Improvements and Remission of Prediabetes and Type 2 Diabetes: Results From a Multidomain Lifestyle Intervention Clinic. Article. Canadian Journal of Diabetes. 2023;47(2):185-189. doi:10.1016/j.jcjd.2022.10.010 | Intervention or Exposure
230 | Author NR, rct 20180201038585N. The effect of DASH diet in subjects with metabolic syndrome. Trial registry record; Clinical trial protocol. https://trialsearch.who.int/Trial2.aspx?TrialID=IRCT20180201038585N12. 2022. | Publication Status
231 | Author NR. The effect of aerobic training and DASH diet on insulin resistance and sex hormones in women with polycystic ovary syndrome. https://trialsearch.who.int/Trial2.aspx?TrialID=IRCT20211106052979N1. 2021. | Publication Status; Study Duration
232 | Ismael S, Silvestre MP, Vasques M, et al. Gut microbial richness as an earlier biomarker of Mediterranean diet intervention in type 2 diabetes metabolic control. Proceedings of the Nutrition Society. 2021;80:1-1. | Publication Status
233 | Ismael S, Silvestre MP, Vasques M, et al. A Pilot Study on the Metabolic Impact of Mediterranean Diet in Type 2 Diabetes: Is Gut Microbiota the Key? Nutrients. Apr 8 2021;13(4) | Study Design, Health Status
234 | Issa BG, Harvie M, McDiarmid S, et al. Manchester Intermittent versus Daily diet Diabetes App Study (MIDDAS). Pilot RCT comparing a continuous with an intermittent low energy diet in patients with type 2 diabetes. Journal: Conference Abstract. Diabetologia. 2020;63(SUPPL 1):S104–S105. | Health Status, Study Duration
235 | Ivan CR, Messina A, Cibelli G, et al. Italian Ketogenic Mediterranean Diet in Overweight and Obese Patients with Prediabetes or Type 2 Diabetes. Nutrients. Oct 18 2022;14(20)doi:10.3390/nu14204361 | Study Duration
236 | Izaola O, Primo D, De Luis D. Dietary Intervention during 9 Months with a Hypocaloric Diet, Interaction of the Genetic Variant of Adiponectin Gene rs822393 with Metabolic Parameters. Article. Disease Markers. 2022;2022doi:10.1155/2022/7058389 | Study Design, Intervention or Exposure
237 | Jannasch F, Kröger J, Agnoli C, et al. Generalizability of a Diabetes-Associated Country-Specific Exploratory Dietary Pattern Is Feasible across European Populations. Article. Journal of Nutrition. 2019;149(6):1047-1055. | Study Design
238 | Jenkins DJA, Srichaikul K, Kendall CWC, Sievenpiper JL. Bean, fruit, and vegetable fiber, but not cereal fiber are associated with reduced mortality in Japan. American Journal of Clinical Nutrition. 2020;111(5):941-943. | Publication Status
239 | Jeziorek M, Szuba A, Kujawa K, Regulska-Ilow B. The Effect of a Low-Carbohydrate, High-Fat Diet versus Moderate-Carbohydrate and Fat Diet on Body Composition in Patients with Lipedema. Diabetes Metab Syndr Obes. 2022;15:2545-2561. doi:10.2147/DMSO.S377720 | Intervention or Exposure, Outcome
240 | Jia YM, Guo DX, Sun LL, et al. Diet, Lifestyle Behaviours and Other Risk Factors Associated With Type 2 Diabetes Beyond Body Mass Index: A Mendelian Randomization Study. Canadian Journal of Diabetes. Dec 2022;46(8):822-828. doi:10.1016/j.jcjd.2022.06.001 | Intervention or Exposure
241 | Jin SM, Ahn J, Park J, Hur KY, Kim JH, Lee MK. East Asian Diet-Mimicking Diet Plan Based on the Mediterranean Diet and the DASH Diet in Adults with Type 2 Diabetes: a Randomized Controlled Trial. Journal: Article in Press. Journal of diabetes investigation. 2020; | Health Status
242 | Johansson A, Acosta S, Mutie PM, Sonestedt E, Engström G, Drake I. Components of a healthy diet and different types of physical activity and risk of atherothrombotic ischemic stroke: A prospective cohort study. Article. Frontiers in Cardiovascular Medicine. 2022;9doi:10.3389/fcvm.2022.993112 | Outcome
243 | Jospe MR, Roy M, Brown RC, et al. Intermittent fasting, Paleolithic, or Mediterranean diets in the real world: exploratory secondary analyses of a weight-loss trial that included choice of diet and exercise. American Journal of Clinical Nutrition. 2020;111(3):503-514. | Size of Study Groups
244 | Goode JP, Smith KJ, Breslin M, et al. A healthful plant-based eating pattern is longitudinally associated with higher insulin sensitivity in Australian adults. The Journal of nutrition. Mar 2023 2023;doi:10.1016/j.tjnut.2023.03.017 | Size of Study Groups
245 | Juna CF, Cho Y, Ham D, Joung H. Association of carbohydrate and fat intake with prevalence of metabolic syndrome can be modified by physical activity and physical environment in ecuadorian adults: The ensanut-ecu study. Article. Nutrients. 2021;13(6)doi:10.3390/nu13061834 | Study Design
246 | Kafyra M, Kalafati IP, Katsareli EA, et al. The iMPROVE Study; Design, Dietary Patterns, and Development of a Lifestyle Index in Overweight and Obese Greek Adults. Nutrients. Oct 3 2021;13(10)doi:10.3390/nu13103495 | Study Design, Outcome
247 | Kahleova H, Berrien-Lopez R, Holtz D, et al. Nutrition for Hospital Workers During a Crisis: Effect of a Plant-Based Dietary Intervention on Cardiometabolic Outcomes and Quality of Life in Healthcare Employees During the COVID-19 Pandemic. Am J Lifestyle Med. May-Jun 2022;16(3):399-407. doi:10.1177/15598276211050339 | Intervention or Exposure
248 | Kahleova H, McCann J, Alwarith J, et al. A plant-based diet in overweight adults in a 16-week randomized clinical trial: The role of dietary acid load. Clin Nutr ESPEN. Aug 2021;44:150-158. doi:10.1016/j.clnesp.2021.05.015 | Intervention or Exposure, Outcome
249 | Kahleova H, Rembert E, Nowak A, Holubkov R, Barnard ND. Effect of a diet intervention on cardiometabolic outcomes: Does race matter? A randomized clinical trial. 41 | Intervention or Exposure
250 | Kahleova H, Hlozkova A, Fleeman R, Fletcher K, Holubkov R, Barnard ND. Fat quantity and quality, as part of a low-fat, vegan diet, are associated with changes in body composition, insulin resistance, and insulin secretion. A 16-week randomized controlled trial. Article. Nutrients. 2019;11(3) | Intervention or Exposure, Comparator
251 | Kahleova H, Petersen KF, Shulman GI, et al. A dietary intervention to alter insulin sensitivity, intramyocellular and hepatocellular lipids, postprandial metabolism, and body weight: a 16-week randomised trial. Journal: Conference Abstract. Diabetologia. 2020;63(SUPPL 1):S16–S17. | Publication Status
252 | Kahleova H, Petersen KF, Shulman GI, et al. Effect of a Low-Fat Vegan Diet on Body Weight, Insulin Sensitivity, Postprandial Metabolism, and Intramyocellular and Hepatocellular Lipid Levels in Overweight Adults: A Randomized Clinical Trial. JAMA Netw Open. Nov 2 2020;3(11):e2025454. | Intervention or Exposure, Comparator
253 | Kahleova H, Rembert E, Alwarith J, et al. Effects of a Low-Fat Vegan Diet on Gut Microbiota in Overweight Individuals and Relationships with Body Weight, Body Composition, and Insulin Sensitivity. A Randomized Clinical Trial. Nutrients. Sep 24 2020;12(10) | Intervention or Exposure
254 | Kalam F, Gabel K, Cienfuegos S, et al. Changes in subjective measures of appetite during 6 months of alternate day fasting with a low carbohydrate diet. Article. Clinical Nutrition ESPEN. 2021;41:417-422. | Intervention or Exposure
255 | Kalam F, Gabel K, Cienfuegos S, et al. Alternate day fasting combined with a low-carbohydrate diet for weight loss, weight maintenance, and metabolic disease risk reduction. Article. Obesity Science and Practice. 2019;5(6):531-539. | Intervention or Exposure
256 | Kalkuz S, Demircan A. Effects of the Mediterranean diet adherence on body composition, blood parameters and quality of life in adults. Postgrad Med J. Nov 12 2020; | Study Design
257 | Kauffman SAE, Averill MM, Delaney JAC, Lemaitre RN, Howard BV, Fretts AM. Associations of diet quality and blood serum lipoprotein levels in a population at high risk for diabetes: the Strong Heart Family Study. Eur J Clin Nutr. Jul 2020;74(7):1084-1090. | Outcome
258 | Kawada T. Egg consumption and incident type 2 diabetes: A risk assessment. Clinical Nutrition. 2021;40(11):5417-5417. | Publication Status
259 | Kawada T. Red meat consumption and biological markers of metabolic disorders. 2021;60:2999-3000. | Publication Status
260 | Keenan S, Cooke MB, Chen WS, Wu S, Belski R. The Effects of Intermittent Fasting and Continuous Energy Restriction with Exercise on Cardiometabolic Biomarkers, Dietary Compliance, and Perceived Hunger and Mood: Secondary Outcomes of a Randomised, Controlled Trial. Nutrients. Jul 26 2022;14(15)doi:10.3390/nu14153071 | Intervention or Exposure, Outcome
261 | Kenđel Jovanović G, Mrakovcic-Sutic I, Pavičić Žeželj S, et al. Metabolic and Hepatic Effects of Energy-Reduced Anti-Inflammatory Diet in Younger Adults with Obesity. Article. Canadian Journal of Gastroenterology and Hepatology. 2021;2021 | Intervention or Exposure
262 | Kendel Jovanovic G, Mrakovcic-Sutic I, Pavicic Zezelj S, Susa B, Rahelic D, Klobucar Majanovic S. The Efficacy of an EnergyRestricted Anti-Inflammatory Diet for the Management of Obesity in Younger Adults. Nutrients. Nov 22 2020;12(11) | Intervention or Exposure
263 | Kerr JA, Liu RS, Gasser CE, et al. Diet quality trajectories and cardiovascular phenotypes/metabolic syndrome risk by 11-12 years. Int J Obes (Lond). Jul 2021;45(7):1392-1403. doi:10.1038/s41366-021-00800-x | Intervention or Exposure, Outcome
264 | Kesary Y, Avital K, Hiersch L. Maternal plant-based diet during gestation and pregnancy outcomes. Arch Gynecol Obstet. Oct 2020;302(4):887-898. | Study Design
265 | Kesse-Guyot E, Rebouillat P, Payrastre L, et al. Prospective association between organic food consumption and the risk of type 2 diabetes: findings from the NutriNet-Sante cohort study. Int J Behav Nutr Phys Act. Nov 9 2020;17(1):136. | Intervention or Exposure
266 | Khan I, Kwon M, Shivappa N, R. Hebert J K. Proinflammatory Dietary Intake is Associated with Increased Risk of Metabolic Syndrome and Its Components: Results from the Population-Based Prospective Study. Nutrients. Apr 24 2020;12(4) | Intervention or Exposure
267 | Kharmats AY, Popp C, Hu L, et al. A randomized clinical trial comparing low-fat versus precision nutrition-based diets for weight loss: impact on glycemic variability and HbA1c. | Intervention or Exposure
268 | Khoury N, Gómez-Donoso C, Martínez MA, et al. Associations Between the Modified Food Standard Agency Nutrient Profiling System Dietary Index and Cardiovascular Risk Factors in an Elderly Population. Front Nutr. Jul 14 2022;9doi:10.3389/fnut.2022.897089 | Outcome
269 | Killeen SL, Phillips CM, Delahunt A, et al. Effect of an Antenatal Lifestyle Intervention on Dietary Inflammatory Index and Its Associations with Maternal and Fetal Outcomes: A Secondary Analysis of the PEARS Trial. Nutrients. Aug 15 2021;13(8)doi:10.3390/nu13082798 | Intervention or Exposure
270 | Kim J, Kim M, Shin Y, Cho JH, Lee D, Kim Y. Association between Dietary Diversity Score and Metabolic Syndrome in Korean Adults: A Community-Based Prospective Cohort Study. Nutrients. Dec 2022;14(24)doi:10.3390/nu14245298 | Intervention or Exposure
271 | Kim MJ, Hur HJ, Jang DJ, Kim MS, Park S, Yang HJ. Inverse association of a traditional Korean diet composed of a multigrain rice-containing meal with fruits and nuts with metabolic syndrome risk: The KoGES. Front Nutr. 2022;9:1051637. doi:10.3389/fnut.2022.1051637 | Study Design
272 | Kim Y, Kim YM, Shin MH, Koh SB, Chang Kim H, Kim MK. Empirically identified dietary patterns and metabolic syndrome risk in a prospective cohort study: The Cardiovascular Disease Association Study. Clin Nutr. Oct 2022;41(10):2156-2162. doi:10.1016/j.clnu.2022.07.038 | Outcome
273 | Kim H, Lee K, Rebholz CM, Kim J. Association between unhealthy plant-based diets and the metabolic syndrome in adult men and women: a population-based study in South Korea. Br J Nutr. Mar 14 2021;125(5):577-590. | Study Design
274 | Kim H, Lee K, Rebholz CM, Kim J. Plant-based diets and incident metabolic syndrome: Results from a South Korean prospective cohort study. PLoS Med. Nov 2020;17(11):e1003371. | Outcome
275 | Kim HS, Lee H, Provido SMP, et al. Association Between Diet Quality and Prevalence of Obesity, Dyslipidemia, and Insulin Resistance Among Filipino Immigrant Women in Korea: The Filipino Women’s Diet and Health Study. Front Public Health. 2021;9:647661. | Study Design
276 | Kim MJ, Lim HS, Lee HH, Kim TH, Park Y. Dietary assessment, nutrition knowledge, and pregnancy outcome in high-risk pregnant Korean women. Article. Clinical and Experimental Obstetrics and Gynecology. 2021;48(5):1178-1185. doi:10.31083/j.ceog4805188 | Intervention or Exposure, Comparator
277 | Kim MJ, Park S, Yang HJ, et al. Alleviation of Dyslipidemia via a Traditional Balanced Korean Diet Represented by a Low Glycemic and Low Cholesterol Diet in Obese Women in a Randomized Controlled Trial. Article. Nutrients. 2022;14(2)doi:10.3390/nu14020235 | Study Duration
278 | Kim SH, Kim HJ, Shin G. Self-Management Mobile Virtual Reality Program for Women with Gestational Diabetes. Int J Environ Res Public Health. Feb 5 2021;18(4) | Intervention or Exposure
279 | Kinnunen T, Liu Y, Koivisto A, Maija V, Suvi L. Effects of dietary counselling on micronutrient intakes in pregnant women in Finland. Maternal & Child Nutrition. 2021;17(4):1-10. | Intervention or Exposure
280 | Koeder C, Kranz RM, Anand C, et al. Effect of a 1-Year Controlled Lifestyle Intervention on Body Weight and Other Risk Markers (the Healthy Lifestyle Community Programme, Cohort 2). Obes Facts. 2022;15(2):228-239. doi:10.1159/000521164 | Intervention or Exposure, Comparator
281 | Kohl J, Brame J, Hauff P, et al. Effects of a Web-Based Weight Loss Program on the Healthy Eating Index-NVS in Adults with Overweight or Obesity and the Association with Dietary, Anthropometric and Cardiometabolic Variables: A Randomized Controlled Clinical Trial. Article. Nutrients. 2023;15(1)doi:10.3390/nu15010007 | Size of Study Groups
282 | Koloverou E, Panagiotakos DB, Georgousopoulou EN, et al. Dietary patterns and 10-year (2002-2012) incidence of type 2 diabetes: Results from the ATTICA cohort study. Article. Review of Diabetic Studies. 2016;13(4):246-256. doi:10.1900/RDS.2016.13.246 | Publication Date
283 | Korat AVA, Li Y, Sacks F, et al. Dairy fat intake and risk of type 2 diabetes in 3 cohorts of US men and women. American Journal of Clinical Nutrition. 2019;110(5):1192-1200. | Intervention or Exposure
284 | Kouvari M, Tsiampalis T, Kosti RI, et al. Quality of plant-based diets is associated with liver steatosis, which predicts type 2 diabetes incidence ten years later: Results from the ATTICA prospective epidemiological study. Clinical Nutrition. Oct 2022;41(10):2094-2102. doi:10.1016/j.clnu.2022.07.026 | Study Design, Outcome
285 | Kouvari M, Boutari C, Chrysohoou C, et al. Mediterranean diet is inversely associated with steatosis and fibrosis and decreases ten-year diabetes and cardiovascular risk in NAFLD subjects: Results from the ATTICA prospective cohort study. Clin Nutr. May 2021;40(5):3314-3324. | Intervention or Exposure, Comparator, Outcome
286 | Kouvari M, Panagiotakos DB, Yannakoulia M, et al. Transition from metabolically benign to metabolically unhealthy obesity and 10-year cardiovascular disease incidence: The ATTICA cohort study. Article. Metabolism: Clinical and Experimental. 2019;93:18-24. | Intervention or Exposure, Outcome
287 | Koyuncu Z, Kadak MT, Tarakçıoğlu MC, Bingöl Çağlayan RH, Doğangün B, Ercan O. Eatıng behavıours and alexıthymıc features of obese and overweıght adolescents. Article in Press. Pediatrics international: official journal of the Japan Pediatric Society. 2021;doi:10.1111/ped.15008 | Intervention or Exposure
288 | Kunath J, Günther J, Rauh K, et al. Effects of a lifestyle intervention during pregnancy to prevent excessive gestational weight gain in routine care - the cluster-randomised GeliS trial. Article. BMC Medicine. 2019;17(1) | Intervention or Exposure
289 | Kunduraci YE, Ozbek H. Does the Energy Restriction Intermittent Fasting Diet Alleviate Metabolic Syndrome Biomarkers? A Randomized Controlled Trial. Nutrients. Oct 21 2020;12(10) | Intervention or Exposure
290 | Kwon YJ, Park K, Lee JH. Low-protein diet is inversely related to the incidence of chronic kidney disease in middle-aged and older adults: results from a community-based prospective cohort study. Article in Press. European journal of nutrition. 2022;doi:10.1007/s00394-022-02981-1 | Intervention or Exposure, Outcome
291 | Lafrenière J, Carbonneau E, Laramée C, et al. Is the Canadian healthy eating index 2007 an appropriate diet indicator of metabolic health? insights from dietary pattern analysis in the PREDISE study. Article. Nutrients. 2019;11(7) | Study Design
292 | Lagstrom H, Stenholm S, Akbaraly T, et al. Diet quality as a predictor of cardiometabolic disease-free life expectancy: the Whitehall II cohort study. Am J Clin Nutr. Apr 1 2020;111(4):787-794. | Outcome
293 | Lai JS, Colega MT, Godfrey KM, et al. Changes in Diet Quality from Pregnancy to 6 Years Postpregnancy and Associations with Cardiometabolic Risk Markers. Nutrients. Apr 13 2023;15(8)doi:10.3390/nu15081870 | Size of Study Groups
294 | Lai KZH, Semnani-Azad Z, Retnakaran R, Harris SB, Hanley AJ. Changes in adiposity mediate the associations of diet quality with insulin sensitivity and beta-cell function. Nutr Metab Cardiovasc Dis. Oct 28 2021;31(11):3054-3063. doi:10.1016/j.numecd.2021.07.025 | Size of Study Groups
295 | Lakka TA, Aittola K, Jarvela-Reijonen E, et al. Real-world effectiveness of digital and group-based lifestyle interventions as compared with usual care to reduce type 2 diabetes risk - A stop diabetes pragmatic randomised trial. Lancet Reg Health-Eu. Jan 2023;24:100527. doi:10.1016/j.lanepe.2022.100527 | Intervention or Exposure
296 | Lakka TA, Lintu N, Vaisto J, et al. A 2 year physical activity and dietary intervention attenuates the increase in insulin resistance in a general population of children: the PANIC study. Diabetologia. Nov 2020;63(11):2270-2281. | Intervention or Exposure
297 | Laouali N, Berrandou T, A. Rothwell J S, et al. Profiles of Polyphenol Intake and Type 2 Diabetes Risk in 60,586 Women Followed for 20 Years: Results from the E3N Cohort Study. Nutrients. Jun 29 2020;12(7) | Intervention or Exposure
298 | Lavie M, Lavie I, Maslovitz S. Paleolithic diet during pregnancy-A potential beneficial effect on metabolic indices and birth weight. Eur J Obstet Gynecol Reprod Biol. Nov 2019;242:7-11. | Study Design
299 | Lawrence RL, Wall CR, Bloomfield FH. Adherence to Dietary Guidelines among Women with and without Gestational Diabetes: Evidence from the Growing Up in New Zealand Study. Article. Nutrients. 2022;14(10)doi:10.3390/nu14102145 | Study Design, Intervention or Exposure
300 | Lawrence RL, Wall CR, Bloomfield FH. Dietary Patterns and Dietary Adaptations in Women with and without Gestational Diabetes: Evidence from the Growing Up in New Zealand Study. Nutrients. Jan 15 2020;12(1) | Study Design
301 | Lee KW, Shin D. Interactions between Bitter Taste Receptor Gene Variants and Dietary Intake Are Associated with the Incidence of Type 2 Diabetes Mellitus in Middle-Aged and Older Korean Adults. International Journal of Molecular Sciences. Feb 2023;24(3)doi:10.3390/ijms24032199 | Intervention or Exposure
302 | Lee KW, Shin D. Positive association between dietary acid load and future insulin resistance risk: findings from the Korean Genome and Epidemiology Study. Nutrition Journal. Dec 8 2020;19(1)doi:10.1186/s12937-020-00653-6 | Intervention or Exposure
303 | Lee DH, Fung TT, Tabung FK, et al. Dietary Pattern and Risk of Multiple Myeloma in Two Large Prospective US Cohort Studies. Article. JNCI cancer spectrum. 2019;3(2):pkz025. doi:10.1093/jncics/pkz025 | Outcome
304 | Lee HA, Park H. Substitution of Carbohydrates for Fats and Risk of Type 2 Diabetes among Korean Middle-Aged Adults: Findings from the Korean Genome and Epidemiology Study. Article. Nutrients. 2022;14(3)doi:10.3390/nu14030654 | Intervention or Exposure
305 | Lehtovirta M, Matthews LA, Laitinen TT, et al. Achievement of the Targets of the 20-Year Infancy-Onset Dietary Intervention— Association with Metabolic Profile from Childhood to Adulthood. Nutrients. 2021;13(2):533-533. | Intervention or Exposure
306 | Levy RB, Rauber F, Chang K, et al. Ultra-processed food consumption and type 2 diabetes incidence: A prospective cohort study. Clinical Nutrition. 2021;40(5):3608-3614. | Intervention or Exposure
307 | Ley SH, Chavarro JE, Li M, et al. Lactation Duration and Long-term Risk for Incident Type 2 Diabetes in Women With a History of Gestational Diabetes Mellitus. Diabetes Care. Apr 2020;43(4):793-798. | Intervention or Exposure
308 | Li L, Shan ZL, Wan ZZ, et al. Associations of lower-carbohydrate and lower-fat diets with mortality among people with prediabetes. American Journal of Clinical Nutrition. Jul 6 2022;116(1):206-215. doi:10.1093/ajcn/nqac058 | Study Design, Intervention or Exposure
309 | Li L, Wan Z, Geng T, et al. Associations of healthy dietary patterns with mortality among people with prediabetes. Eur J Nutr. Apr 2023;62(3):1377-1387. doi:10.1007/s00394-022-03078-5 | Study Design, Outcome
310 | Li Y, Yatsuya H, Wang C, et al. Dietary Patterns Derived from Reduced Rank Regression Are Associated with the 5-Year Occurrence of Metabolic Syndrome: Aichi Workers’ Cohort Study. Nutrients. Jul 22 2022;14(15)doi:10.3390/nu14153019 | Outcome
311 | Li LJ, Aris IM, Han WM, Tan KH. A Promising Food-Coaching Intervention Program to Achieve Optimal Gestational Weight Gain in Overweight and Obese Pregnant Women: Pilot Randomized Controlled Trial of a Smartphone App. JMIR Form Res. Oct 24 2019;3(4):e13013. doi:10.2196/13013 | Intervention or Exposure, Outcome
312 | Li M, Lin Q, Shi J, et al. The impact of lifestyle intervention on dietary quality among rural women with previous gestational diabetes mellitus— a randomized controlled study. Article. Nutrients. 2021;13(8)doi:10.3390/nu13082642 | Outcome
313 | Li M, Shi Z. Association between Ultra-Processed Food Consumption and Diabetes in Chinese Adults—Results from the China Health and Nutrition Survey. Article. Nutrients. 2022;14(20). doi:10.3390/nu14204241 | Country
314 | Li M, Li S, Chavarro JE, et al. Prepregnancy habitual intakes of total, supplemental, and food folate and risk of gestational diabetes mellitus: A prospective cohort study. Article. Diabetes Care. 2019;42(6):1034-1041. doi:10.2337/dc18-2198 | Intervention or Exposure, Comparator
315 | Li M, Rahman ML, Wu J, et al. Genetic factors and risk of type 2 diabetes among women with a history of gestational diabetes: findings from two independent populations. BMJ Open Diabetes Res Care. Jan 2020;8(1). doi:10.1136/bmjdrc-2019-000850 | Intervention or Exposure
316 | Li M, Shi J, Luo J, et al. Diet Quality among Women with Previous Gestational Diabetes Mellitus in Rural Areas of Hunan Province. Int J Environ Res Public Health. Aug 16 2020;17(16). doi:10.3390/ijerph17165942 | Health Status, Outcome
317 | Li Y, Schoufour J, Wang DD, et al. Healthy lifestyle and life expectancy free of cancer, cardiovascular disease, and type 2 diabetes: prospective cohort study. BMJ. Jan 8 2020;368:l6669. doi:10.1136/bmj.l6669 | Outcome
318 | Liang Z, Wang L, Liu H, et al. Genetic susceptibility, lifestyle intervention and glycemic changes among women with prior gestational diabetes. Clin Nutr. Jul 2020;39(7):2144-2150. doi:10.1016/j.clnu.2019.08.032 | Intervention or Exposure
319 | Liedes H, Mattila E, Honka A, et al. Associations Between Engagement with the BitHabit Digital Lifestyle Intervention and Changes in Type 2 Diabetes Risk Factors. Stud Health Technol Inform. 2023 May 18;302:1009-1010. doi: 10.3233/SHTI230328. | Intervention or Exposure
320 | Lim SX, Cox V, Rodrigues N, et al. Evaluation of Preconception Dietary Patterns in Women Enrolled in a Multisite Study. Article. Current Developments in Nutrition. 2022;6(7). doi:10.1093/cdn/nzac106 | Study Design
321 | Lin LY, Hsu CY, Chiou HY, et al. Association between Dietary Patterns and Serum Hepatic Enzyme Levels in Adults with Dyslipidemia and Impaired Fasting Plasma Glucose. Nutrients. Mar 18 2021;13(3). doi:10.3390/nu13030987 | Study Design, Outcome
322 | Lin R, Chien KL, Tsai MC, Wang YJ, Hsu LY. Association between a priori and a posteriori dietary patterns and the risk of type 2 diabetes: A representative cohort study in Taiwan. Article. Journal of Nutritional Science. 2023;12doi:10.1017/jns.2023.8 | Country
323 | Lin TJ, Tang SC, Liao PY, Dongoran RA, Yang JH, Liu CH. A comparison of L-carnitine and several cardiovascular-related biomarkers between healthy vegetarians and omnivores. Nutrition. 2019. 66:29-37. doi:10.1016/j.nut.2019.03.019 | Study Design, Intervention or Exposure
324 | Lindsay KL, Most J, Buehler K, Kebbe M, Altazan AD, Redman LM. Maternal mindful eating as a target for improving metabolic outcomes in pregnant women with obesity. Frontiers in Bioscience-Landmark. Dec 30 2021;26(12):1548-1558. doi:10.52586/5048 | Intervention or Exposure
325 | Linke CS, Kelly J, Karlsen M, Pollard K, Trapp C. Type 2 Diabetes Prevention and Management With a Low-Fat, Whole-Food, Plant-Based Diet. J Fam Pract. Jan 2022;71(Suppl 1 Lifestyle):S41-S47. doi:10.12788/jfp.0252 | Study Design
326 | Lisón JF, Palomar G, Mensorio MS, et al. Impact of a Web-Based Exercise and Nutritional Education Intervention in Patients Who Are Obese with Hypertension: Randomized Wait-List Controlled Trial. Journal of Medical Internet Research. 2020. 22. doi:10.2196/14196 | Intervention or Exposure
327 | Liu Q, Wen Q, Lv J, et al. The Prospective Associations of Lipid Metabolism-Related Dietary Patterns with the Risk of Diabetes in Chinese Adults. Nutrients. Feb 25 2022;14(5)doi:10.3390/nu14050980 | Country
328 | Liu YH, Lu LP, Yi MH, et al. Study on the correlation between homocysteine-related dietary patterns and gestational diabetes mellitus:a reduced-rank regression analysis study. BMC Pregnancy Childbirth. 2022 Apr 10;22(1):306. doi: 10.1186/s12884-022-04656-5. | Study Design
329 | Liu M, Liu C, Zhang Z, et al. Quantity and variety of food groups consumption and the risk of diabetes in adults: A prospective cohort study. Clinical Nutrition. 2021. 40:5710-5717. doi:10.1016/j.clnu.2021.10.003 | Intervention or Exposure
330 | Liu X, Zheng Y, Guasch-Ferré M, et al. High plasma glutamate and low glutamine-to-glutamate ratio are associated with type 2 diabetes: Case-cohort study within the PREDIMED trial. Nutrition, Metabolism and Cardiovascular Diseases. 29:1040-1049. doi:10.1016/j.numecd.2019.06.005 | Intervention or Exposure
331 | Livingstone KM, Milte CM, Torres SJ, et al. Nineteen-Year Associations between Three Diet Quality Indices and All-Cause and Cardiovascular Disease Mortality: The Australian Diabetes, Obesity, and Lifestyle Study. Journal of Nutrition. Mar 3 2022;152(3):805-815. doi:10.1093/jn/nxab386 | Outcome
332 | Lönnberg L, Ekblom-Bak E, Damberg M. Improved unhealthy lifestyle habits in patients with high cardiovascular risk: results from a structured lifestyle programme in primary care. Article. Upsala journal of medical sciences. 2019. 124:94-104. doi:10.1080/03009734.2019.1602088 | Study Design, Intervention or Exposure
333 | Lonnie M, Wadolowska L, Morze J, Bandurska-Stankiewicz E. Associations of Dietary-Lifestyle Patterns with Obesity and Metabolic Health: Two-Year Changes in MeDiSH(®) Study Cohort. Int J Environ Res Public Health. 2022 Oct 21;19(20):13647. doi: 10.3390/ijerph192013647. | Intervention or Exposure, Comparator
334 | Looman M, Geelen A, Samlal RAK, et al. Changes in micronutrient intake and status, diet quality and glucose tolerance from preconception to the second trimester of pregnancy. Nutrients. 2019. 11. doi:10.3390/nu11020460 | Data Overlap
335 | Lopez-Contreras IN, Vilchis-Gil J, Klunder-Klunder M, Villalpando-Carrion S, Flores-Huerta S. Dietary habits and metabolic response improve in obese children whose mothers received an intervention to promote healthy eating: randomized clinical trial. BMC Public Health. Aug 14 2020;20(1):1240. | Intervention or Exposure
336 | Lopez-Olmedo N, Jonnalagadda S, Basto-Abreu A, et al. Adherence to Dietary Guidelines in Adults by Diabetes Status: Results From the 2012 Mexican National Health and Nutrition Survey. Nutrients. 2020. 12. doi:10.3390/nu12113464 | Study Design
337 | Lotfaliany M, Mansournia MA, Azizi F, et al. Long-term effectiveness of a lifestyle intervention on the prevention of type 2 diabetes in a middle-income country. Sci Rep. 2020. 10:14173. doi:10.1038/s41598-020-71119-2 | Intervention or Exposure
338 | Lotfi MH, Fallahzadeh H, Rahmanian M, et al. Association of food groups intake and physical activity with gestational diabetes mellitus in Iranian women. J Matern Fetal Neonatal Med. 2020. 33:3559-3564. doi:10.1080/14767058.2019.1579189 | Study Design
339 | Lowe DA, Wu N, Rohdin-Bibby L, et al. Effects of Time-Restricted Eating on Weight Loss and Other Metabolic Parameters in Women and Men with Overweight and Obesity: The TREAT Randomized Clinical Trial. Article. JAMA Internal Medicine. 2020. 180:1491-1499. doi:10.1001/jamainternmed.2020.4153 | Intervention or Exposure
340 | Lu D, Yuan Z, Yang L, et al. Body Composition and Metabolic Improvement in Patients Followed up by a Multidisciplinary Team for Obesity in China. Article. Journal of Diabetes Research. 2021;2021doi:10.1155/2021/8862217 | Intervention or Exposure
341 | Luo Y, Wang J, Sun L, et al. Isocaloric-restricted Mediterranean Diet and Chinese Diets High or Low in Plants in Adults With Prediabetes. J Clin Endocrinol Metab. Jul 14 2022;107(8):2216-2227. doi:10.1210/clinem/dgac303 | Outcome
342 | Lüscher, TF. Nutrition, obesity, diabetes, and cardiovascular outcomes: A deadly association. European Heart Journal. 2020. 41:2603-2607. doi:10.1093/eurheartj/ehaa622 | Publication Status
343 | Lynch EB, Mack L, Avery E, et al. Randomized Trial of a Lifestyle Intervention for Urban Low-Income African Americans with Type 2 Diabetes. Article. Journal of General Internal Medicine. 2019. 34:1174-1183. doi:10.1007/s11606-019-04894-y | Intervention or Exposure, Health Status
344 | Madlala SS, Hill J, Kunneke E, Kengne AP, Peer N, Faber M. Dietary Diversity and its Association with Nutritional Status, Cardiometabolic Risk Factors and Food Choices of Adults at Risk for Type 2 Diabetes Mellitus in Cape Town, South Africa. Nutrients. Aug 2022;14(15)doi:10.3390/nu14153191 | Study Design
345 | Magkos F, Rasmussen SI, Hjorth MF, et al. Unprocessed red meat in the dietary treatment of obesity: a randomized controlled trial of beef supplementation during weight maintenance after successful weight loss. Am J Clin Nutr. Dec 19 2022;116(6):1820-1830. doi:10.1093/ajcn/nqac152 | Intervention or Exposure
346 | Mahdavi S, Jenkins DJA, El-Sohemy A. Genetic variation in 9p21, dietary patterns, and insulin sensitivity. Front Genet. 2022;13:988873. doi:10.3389/fgene.2022.988873 | Study Design, Comparator
347 | Mahjoub F, Ben Jemaa H, Ben Sabeh F, Ben Amor N, Gamoudi A, Jamoussi H. Impact of nutrients and Mediterranean diet on the occurrence of gestational diabetes. Article. Libyan Journal of Medicine. 2021;16(1) | Study Design
348 | Mahmoudinezhad M, Abbasalizad Farhangi M. Association between Ag-RP, alpha-MSH and cardiovascular risk factors regarding adherence to diet quality index-international (DQI-I) among obese individuals. 13(4) | Study Design
349 | Mak JKL, Pham NM, Lee AH, et al. Dietary patterns during pregnancy and risk of gestational diabetes: A prospective cohort study in Western China. Article. Nutrition Journal. 2018;17(1)doi:10.1186/s12937-018-0413-3 | Data Overlap
350 | Maldonado LE, Farzan SF, Toledo-Corral CM, et al. A Vegetable, Oil, and Fruit Dietary Pattern in Late Pregnancy is Linked to Reduced Risks of Adverse Birth Outcomes in a Predominantly Low-Income Hispanic and Latina Pregnancy Cohort. Journal of Nutrition. Dec 2022;152(12):2837-2846. doi:10.1093/jn/nxac209 | Study Design, Outcome
351 | Maldonado LE, Farzan SF, Toledo-Corral CM, et al. Vegetables, Oils, and Fruit Dietary Pattern in Late Pregnancy is Linked to Reduced Risk of Adverse Birth Outcomes in a Predominantly Low-Income Hispanic/Latina Pregnancy Cohort. | Study Design; Duplicate
352 | Mancioppi V, Solito A, Ricotti R, et al. Good-day: efficacy of gamification of an educational training to mediterranean diet on weight and metabolic control in paediatric obesity. preliminary data at 6 months. Journal: Conference Abstract. High blood pressure & cardiovascular prevention. 2019;26(2):171–172. | Publication Status
353 | Mansourian M, Yazdani A, Faghihimani E, Aminorraya A, Amini M, Jafari-Koshki T. Factors associated with progression to pre-diabetes: a recurrent events analysis. Article. Eating and Weight Disorders. 2020;25(1):135-141. | Study Design, Intervention or Exposure
354 | Martensson A, Stomby A, Tellstrom A, Ryberg M, Waling M, Otten J. Using a Paleo Ratio to Assess Adherence to Paleolithic Dietary Recommendations in a Randomized Controlled Trial of Individuals with Type 2 Diabetes. Nutrients. Mar 17 2021;13(3) | Intervention or Exposure, Health Status
355 | Martin S, Banzer W, Berg A, et al. Prediabetes conversion to normoglycemia is superior adding a low-carbohydrate formula diet to lifestyle intervention-a 12-month subanalysis of the accorh study. Journal: Conference Abstract. Diabetes. 2019;68 | Publication Status
356 | Martinez-Gonzalez MA, Fernandez-Lazaro CI, Toledo E, et al. Carbohydrate quality changes and concurrent changes in cardiovascular risk factors: a longitudinal analysis in the PREDIMED-Plus randomized trial. Am J Clin Nutr. Feb 1 2020;111(2):291-306. | Intervention or Exposure
357 | Martin-Piedra L, Alcala-Diaz JF, Gutierrez-Mariscal FM, et al. Evolution of Metabolic Phenotypes of Obesity in Coronary Patients after 5 Years of Dietary Intervention: From the CORDIOPREV Study. Nutrients. Nov 12 2021;13(11)doi:10.3390/nu13114046 | Health Status
358 | Maskarinec G, Hullar MAJ. Understanding the Interaction of Diet Quality with the Gut Microbiome and Their Effect on Disease. J Nutr. Apr 1 2020;150(4):654-655. | Outcome, Publication Status
359 | Mattavelli E, Olmastroni E, Casula M, et al. Adherence to Mediterranean Diet: A Population-Based Longitudinal Cohort Study. Nutrients. Apr 12 2023;15(8)doi:10.3390/nu15081844 | Size of Study Groups
360 | Mauro AD, Tuccinardi D, Toro RD, et al. 226-OR: The Mediterranean Diet Increases GLP-1 and Oxyntomodulin Compared with Vegetarian Diet in Type 2 Diabetes Subjects. Diabetes. 2020;69:N.PAG-N.PAG. | Publication Status
361 | Mazidi M, Katsiki N, Mikhailidis DP, Banach M. Effect of Dietary Insulinemia on All-Cause and Cause-Specific Mortality: Results From a Cohort Study. Article. Journal of the American College of Nutrition. 2020;39(5):407-413. | Outcome
362 | Mazidi M, Katsiki N, Mikhailidis DP, Bartłomiejczyk MA, Banach M. Association of empirical dietary atherogenic indices with all-cause and cause-specific mortality in a multi-ethnic adult population of the United States. Article. Nutrients. 2019;11(10) | Intervention or Exposure, Outcome
363 | McEvoy CT, Moore SE, Erwin CM, et al. Trial to Encourage Adoption and Maintenance of a MEditerranean Diet (TEAM-MED): a randomised pilot trial of a peer support intervention for dietary behaviour change in adults from a Northern European population at high cardiovascular disease risk. Article in Press. The British journal of nutrition. 2021:1-37. doi:10.1017/S0007114521003986 | Intervention or Exposure, Size of Study Groups
364 | McKenzie AL, Athinarayanan SJ, McCue JJ, et al. Type 2 diabetes prevention focused on normalization of glycemia: A two-year pilot study. Article. Nutrients. 2021;13(3):1-9. | Study Design, Intervention or Exposure
365 | Mei S, Ding J, Wang K, Ni Z, Yu J. Mediterranean Diet Combined With a Low-Carbohydrate Dietary Pattern in the Treatment of Overweight Polycystic Ovary Syndrome Patients. Front Nutr. 2022;9:876620. doi:10.3389/fnut.2022.876620 | Intervention or Exposure
366 | Meinila J, Valkama A, Koivusalo SB, et al. Association between diet quality measured by the Healthy Food Intake Index and later risk of gestational diabetes - A secondary analysis of the RADIEL trial. Article. European Journal of Clinical Nutrition. 2017;71(4):555-557. doi:10.1038/ejcn.2016.275 | Data Overlap
367 | Melero V, Assaf-Balut C, Torre NG, et al. Benefits of Adhering to a Mediterranean Diet Supplemented with Extra Virgin Olive Oil and Pistachios in Pregnancy on the Health of Offspring at 2 Years of Age. Results of the San Carlos Gestational Diabetes Mellitus Prevention Study. J Clin Med. May 13 2020;9(5) | Data Overlap
368 | Menichini D, Petrella E, Dipace V, Di Monte A, Neri I, Facchinetti F. The Impact of an Early Lifestyle Intervention on Pregnancy Outcomes in a Cohort of Insulin-Resistant Overweight and Obese Women. Nutrients. May 21 2020;12(5) | Intervention or Exposure, Comparator
369 | Merino J, Jablonski KA, Mercader JM, et al. Interaction Between Type 2 Diabetes Prevention Strategies and Genetic Determinants of Coronary Artery Disease on Cardiometabolic Risk Factors. Diabetes. Jan 2020;69(1):112-120. | Intervention or Exposure
370 | Meroni A, Muirhead RP, Atkinson FS, Fogelholm M, Raben A, Brand-Miller JC. Is a Higher Protein-Lower Glycemic Index Diet More Nutritious Than a Conventional Diet? A PREVIEW Sub-study. Front Nutr. 2020;7:603801. | Intervention or Exposure
371 | Migliaretti G, Ame C, Ciullo S, et al. Metabolic and psychological effects of short-term increased consumption of less-processed foods in daily diets: A Pilot Study. Article. Diabetes and Metabolism. 2020;46(1):66-69. doi:10.1016/j.diabet.2019.07.002 | Intervention or Exposure
372 | Miller CK, King D, Nagaraja HN, Fujita K, Cheavens J, Focht BC. Impact of an augmented intervention on self-regulatory, dietary and physical activity outcomes in a diabetes prevention trial among adults with prediabetes. J Behav Med. Oct 2023;46(5):770-780. doi:10.1007/s10865-023-00406-w | Intervention or Exposure
373 | Milone G, Chung JH, Haas DM, et al. Periconceptional diet quality predicts glycemic control and gestational diabetes risk in nulliparous women. American Journal of Obstetrics & Gynecology. 2022;226(1):S46-S47. | Publication Status
374 | Minhas AS, Hong X, Wang G, et al. Mediterranean-Style Diet and Risk of Preeclampsia by Race in the Boston Birth Cohort. Article. Journal of the American Heart Association. 2022;11(9)doi:10.1161/JAHA.121.022589 | Study Design
375 | Mirmiran P, Hosseini S, Bahadoran Z, Azizi F. Dietary pattern scores in relation to pre-diabetes regression to normal glycemia or progression to type 2 diabetes: a 9-year follow-up. BMC Endocr Disord. Jan 20 2023;23(1):20. doi:10.1186/s12902-023-01275-9 | Size of Study Groups
376 | Mirmiran P, Ramezan M, Farhadnejad H, Asghari G, Tahmasebinejad Z, Azizi F. High Dietary Diabetes Risk Reduction Score Is Associated with Decreased Risk of Chronic Kidney Disease in Tehranian Adults. Int J Clin Pract. Feb 3 2022;2022doi:10.1155/2022/5745297 | Study Design, Outcome
377 | Mirmiran P, Hosseinpour-Niazi S, Moghaddam-Banaem L, Lamyian M, Goshtasebi A, Azizi F. Inverse relation between fruit and vegetable intake and the risk of gestational diabetes mellitus. Article. International Journal for Vitamin and Nutrition Research. 2019;89(1-2):37-44. | Intervention or Exposure
378 | Mirmiran P, Ziadlou M, Karimi S, Hosseini-Esfahani F, Azizi F. The association of dietary patterns and adherence to WHO healthy diet with metabolic syndrome in children and adolescents: Tehran lipid and glucose study. BMC Public Health. Nov 6 2019;19(1):1457. | Outcome
379 | Mitchell A, Fall T, Melhus H, Wolk A, Michaelsson K, Byberg L. Is the effect of Mediterranean diet on hip fracture mediated through type 2 diabetes mellitus and body mass index? Int J Epidemiol. Mar 3 2021;50(1):234-244. | Outcome
380 | Mitra SR, Tan PY. Effect of an individualised high-protein, energy-restricted diet on anthropometric and cardio-metabolic parameters in overweight and obese Malaysian adults: A 6-month randomised controlled study. Article. British Journal of Nutrition. 2019;121(9):1002-1017. | Intervention or Exposure
381 | Mizgier M, Jarzabek-Bielecka G, Mruczyk K. Maternal diet and gestational diabetes mellitus development. J Matern Fetal Neonatal Med. Jan 2021;34(1):77-86. | Intervention or Exposure
382 | Mohd Y, B N. A low glycemic index diet in the management of gestational diabetes mellitus: the Malaysian experience. Journal: Conference Abstract. Annals of nutrition & metabolism. 2019;75(3):34–35. | Publication Status
383 | Mokhtari E, Farhadnejad H, Teymoori F, Mirmiran P, Azizi F. The association of insulinemic potential of diet and lifestyle with the risk of insulin-related disorders: a prospective cohort study among participants of Tehran Lipid and Glucose Study. Article. Diabetology and Metabolic Syndrome. 2021;13(1)doi:10.1186/s13098-021-00674-z | Outcome
384 | Molina-Leyva A, Cuenca-Barrales C, Vega-Castillo JJ, Ruiz-Carrascosa JC, Ruiz-Villaverde R. Adherence to Mediterranean diet in Spanish patients with psoriasis: Cardiovascular benefits? Article. Dermatologic Therapy. 2019;32(2) | Study Design, Health Status
385 | Montemayor S, Mascaro CM, Ugarriza L, et al. Adherence to Mediterranean Diet and NAFLD in Patients with Metabolic Syndrome: The FLIPAN Study. Nutrients. Aug 3 2022;14(15)doi:10.3390/nu14153186 | Outcome
386 | Mu L, Yu P, Xu H, et al. Efecto de la reducción de sodio basada en la dieta DASH sobre la presión arterial en pacientes hipertensos con diabetes de tipo 2. Article in Press. Effect of sodium reduction based on the DASH diet on blood pressure in hypertensive patients with type 2 diabetes. 2022;doi:10.20960/nh.04039 | Health Status
387 | Mulcahy MC, Tellez-Rojo MM, Cantoral A, et al. Maternal Carbohydrate Intake During Pregnancy is Associated with Child Peripubertal Markers of Metabolic Health but not Adiposity. | Intervention or Exposure
388 | Muralidharan J, Moreno-Indias I, Bullo M, et al. Effect on gut microbiota of a 1-y lifestyle intervention with Mediterranean diet compared with energy-reduced Mediterranean diet and physical activity promotion: PREDIMED-Plus Study. Am J Clin Nutr. Sep 1 2021;114(3):1148-1158. doi:10.1093/ajcn/nqab150 | Intervention or Exposure
389 | Murni IK, Sulistyoningrum DC, Susilowati R, Julia M, Dickinson KM. The association between dietary intake and cardiometabolic risk factors among obese adolescents in Indonesia. Bmc Pediatrics. May 12 2022;22(1)doi:10.1186/s12887-022-03341-y | Study Design
390 | Murphy J. Exercise, healthy diet in midlife may prevent serious health conditions in senior years. 2021. | Publication Status
391 | Murphy KJ, Dyer KA, Hyde B, et al. Long-Term Adherence to a Mediterranean Diet 1-Year after Completion of the MedLey Study. Article. Nutrients. 2022;14(15)doi:10.3390/nu14153098 | Outcome
392 | Muscogiuri G, Barrea L, Di Somma C, et al. Patient empowerment and the Mediterranean diet as a possible tool to tackle prediabetes associated with overweight or obesity: a pilot study. Article. Hormones. 2019;18(1):75-84. | Study Design, Comparator
393 | Mustafa S, Harding J, Wall C, Crowther C. Sociodemographic factors associated with adherence to dietary guidelines in women with gestational diabetes: A cohort study. Article. Nutrients. 2021;13(6)doi:10.3390/nu13061884 | Health Status
394 | Myshak-Davis AT, Evans J, Howay H, Sakakibara BM. The effects of a primary care low-carbohydrate, high-fat dietary educational intervention on laboratory and anthropometric data of patients with chronic disease: a retrospective cohort chart review. Fam Pract. Sep 24 2022;39(5):819-825. doi:10.1093/fampra/cmac003 | Study Design, Intervention or Exposure
395 | Nabila S, Kim JE, Choi J, et al. Associations Between Modifiable Risk Factors and Changes in Glycemic Status Among Individuals With Prediabetes. Diabetes Care. Mar 2023;46(3):535-543. doi:10.2337/dc22-1042 | Intervention or Exposure, Publication Status
396 | Nah EH, Chu J, Kim S, Cho S, Kwon E. Efficacy of lifestyle interventions in the reversion to normoglycemia in Korean prediabetics: One-year results from a randomised controlled trial. Article. Primary Care Diabetes. 2019;13(3):212-220. | Intervention or Exposure
397 | No author field. A Mediterranean Intervention on Prediabetic Children. https://clinicaltrials.gov/show/NCT05424107. 2022. | Publication Status
398 | No author field. Acceptability, Feasibility and Effectiveness of a Worksite Intervention to Lower Cardiometabolic Risk in South Africa. https://clinicaltrials.gov/show/NCT04494139. 2020. | Publication Status
399 | No author field, Healthy Lifestyle Intervention on Diabetes Risk Reduction Among Bruneian Young Adults. https://clinicaltrials.gov/show/NCT04217759. 2020. | Publication Status
400 | No author field. Optimizing Gestational Weight Gain for Prevention of Gestational Diabetes Mellitus in Malaysia. https://clinicaltrials.gov/show/NCT05489536. 2022. | Publication Status
401 | Nguyen HD, Oh H, Kim M-S. Higher intakes of fruits, vegetables, and multiple individual nutrients is associated with a lower risk of metabolic syndrome among adults with comorbidities. Nutrition Research. 2022;99:1-12. | Study Design, Intervention or Exposure
402 | Nilsen I, Andersson A, Laurenius A, Osterberg J, Sundbom M, Haenni A. Lower interstitial glucose concentrations but higher glucose variability during low-energy diet compared to regular diet—an observational study in females with obesity. Article. Nutrients. 2021;13(11)doi:10.3390/nu13113687 | Intervention or Exposure, Study Duration
403 | Njike VY, Kela GCM, Treu JA, et al. Egg Consumption in the Context of Plant-Based Diets and Diet Quality in Adults at Risk for Type 2 Diabetes: A Randomized Single Blind Cross-over Controlled Trial. J Am Nutr Assoc. Feb 17 2023;42(2):130-139. doi:10.1080/07315724.2021.2006824 | Study Duration, Outcome
404 | Njike VY, Treu JA, Kela GCM, Ayettey RG, Comerford BP, Siddiqui WT. Egg Consumption in the Context of Plant-Based Diets and Cardiometabolic Risk Factors in Adults at Risk of Type 2 Diabetes. Article in Press. The Journal of nutrition. 2021;doi:10.1093/jn/nxab283 | Intervention or Exposure, Study Duration
405 | Nouri F, Sadeghi M, Mohammadifard N, Roohafza H, Feizi A, Sarrafzadegan N. Longitudinal association between an overall diet quality index and latent profiles of cardiovascular risk factors: results from a population based 13-year follow up cohort study. Nutr Metab (Lond). Mar 10 2021;18(1):28. | Outcome, Country
406 | O’Brien EC, Geraghty AA, O’Sullivan EJ, et al. Five-year follow up of a low glycaemic index dietary randomised controlled trial in pregnancy—no long-term maternal effects of a dietary intervention. Article. BJOG: An International Journal of Obstetrics and Gynaecology. 2019;126(4):514-524. | Intervention or Exposure, Outcome
407 | O’Hearn M, Erndt-Marino J, Gerber S, et al. Validation of Food Compass with a healthy diet, cardiometabolic health, and mortality among U.S. adults, 1999-2018. 13(1) | Outcome
408 | Okuda M, Fujiwara A, Sasaki S. Adherence to the Japanese Food Guide: The Association between Three Scoring Systems and Cardiometabolic Risks in Japanese Adolescents. 14(1) | Study Design
409 | Oliverio A, Radice P, Colombo M, et al. The Impact of Mediterranean Dietary Intervention on Metabolic and Hormonal Parameters According to BRCA1/2 Variant Type. Article. Frontiers in Genetics. 2022;13doi:10.3389/fgene.2022.820878 | Intervention or Exposure, Comparator
410 | Olsson K, Ramne S, Gonzalez-Padilla E, Ericson U, Sonestedt E. Associations of carbohydrates and carbohydrate-rich foods with incidence of type 2 diabetes. Br J Nutr. Oct 14 2021;126(7):1065-1075. | Intervention or Exposure
411 | O’Reilly S, Versace V, Mohebbi M, Lim S, Janus E, Dunbar J. The effect of a diabetes prevention program on dietary quality in women with previous gestational diabetes. Article. BMC Women’s Health. 2019;19(1) | Comparator
412 | Otten J, Ryberg M, Mellberg C, et al. Postprandial levels of GLP-1, GIP and glucagon after 2 years of weight loss with a Paleolithic diet: A randomised controlled trial in healthy obese women. Article. European Journal of Endocrinology. 2019;180(6):417-427. | Intervention or Exposure, Outcome
413 | Ovaska et al. SUN-PO109: Effects of Western Style or Mediterranean Diet on Insulin Resistance Markers in Female BRCA1/2 Mutation Carriers (Libre Study). Clinical nutrition (Edinburgh, Scotland). 2019. 38:S99–S100. doi:10.1016/S0261-5614(19)32743-8 | Publication Status
414 | Øyen J, Brantsæter AL, Nøstbakken OJ, et al. Intakes of Fish and Long-chain n-3 Polyunsaturated Fatty Acid Supplements During Pregnancy and Subsequent Risk of Type 2 Diabetes in a Large Prospective Cohort Study of Norwegian Women. Article in Press. Diabetes care. 2021;doi:10.2337/dc21-0447 | Intervention or Exposure
415 | No author field. Impact of adding high probiotic food supplements to the diet and yoga on insulin resistance in polycystic ovarian syndrome. Trial registry record; Clinical trial protocol. https://trialsearchwhoint/Trial2aspx?TrialID=PACTR202211578683612. 2022; | Health Status, Publication Status
416 | Pahkala K, Laitinen TT, Niinikoski H, et al. Effects of 20-year infancy-onset dietary counselling on cardiometabolic risk factors in the Special Turku Coronary Risk Factor Intervention Project (STRIP): 6-year post-intervention follow-up. Lancet Child Adolesc Health. May 2020;4(5):359-369. | Intervention or Exposure
417 | Paik JK, Park M, Shin JE, Jang SY, Shin JY. Dietary Protein to Carbohydrate Ratio and Incidence of Metabolic Syndrome in Korean Adults Based on a Long-Term Prospective Community-Based Cohort. Nutrients. Oct 26 2020;12(11) | Intervention or Exposure
418 | Päivärinta E, Itkonen ST, Pellinen T, Lehtovirta M, Erkkola M, Pajari AM. Replacing animal-based proteins with plant-based proteins changes the composition of a whole nordic diet—a randomised clinical trial in healthy Finnish adults. Article. Nutrients. 2020;12(4) | Intervention or Exposure, Outcome
419 | Palmer R. Mediterranean Diet During Pregnancy May Reduce Risk of Metabolic Syndrome. Scan’s Pulse. Winter2021 2021;41(1):21-21. | Publication Status
420 | Paltoglou G, Raftopoulou C, Nicolaides NC, et al. A Comprehensive, Multidisciplinary, Personalized, Lifestyle Intervention Program Is Associated with Increased Leukocyte Telomere Length in Children and Adolescents with Overweight and Obesity. 13(8) | Intervention or Exposure
421 | Pan W, Karatela S, Lu Q, et al. Association of Diet Quality during Pregnancy with Maternal Glucose Metabolism in Chinese Women. | Size of Study Groups
422 | Pandya R, Abdelaal R, Chen JW, et al. Retrospective assessment of metabolic syndrome components in early adult life on vegetarian dietary status. 10 | Intervention or Exposure
423 | Panizza CE, Lim U, Yonemori KM, et al. Effects of intermittent energy restriction combined with a mediterranean diet on reducing visceral adiposity: A randomized active comparator pilot study. Article. Nutrients. 2019;11(6) | Intervention or Exposure, Outcome
424 | Papandreou P, Gioxari A, Daskalou E, Grammatikopoulou MG, Skouroliakou M, Bogdanos DP. Mediterranean Diet and Physical Activity Nudges versus Usual Care in Women with Rheumatoid Arthritis: Results from the MADEIRA Randomized Controlled Trial. 15(3) | Health Status, Outcome
425 | Park S. A Causal and Inverse Relationship between Plant-Based Diet Intake and in a Two-Sample Mendelian Randomization Study. 12(3) | Study Design,
426 | Park S. Association of polygenic risk scores for insulin resistance risk and their interaction with a plant-based diet, especially fruits, vitamin C, and flavonoid intake, in Asian adults. 111 | Study Design, Intervention or Exposure
427 | Park S. Interaction of Polygenetic Variants for Gestational Diabetes Mellitus Risk with Breastfeeding and Korean Balanced Diet to Influence Type 2 Diabetes Risk in Later Life in a Large Hospital-Based Cohort. 11(11) | Study Design, Intervention or Exposure
428 | Park YMM, Choi MK, Lee SS, et al. Dietary inflammatory potential and risk of mortality in metabolically healthy and unhealthy phenotypes among overweight and obese adults. Article. Clinical Nutrition. 2019;38(2):682-688. | Intervention or Exposure, Outcome
429 | Parlapani E, Agakidis C, Karagiozoglou-Lampoudi T, et al. The Mediterranean diet adherence by pregnant women delivering prematurely: association with size at birth and complications of prematurity. Article. Journal of Maternal-Fetal and Neonatal Medicine. 2019;32(7):1084-1091. | Study Design
430 | Parnell LD, Noel SE, Bhupathiraju SN, et al. Metabolite patterns link diet, obesity, and type 2 diabetes in a Hispanic population. 17(10) | Intervention or Exposure
431 | Partula V, Deschasaux M, Druesne-Pecollo N, et al. Associations between consumption of dietary fibers and the risk of cardiovascular diseases, cancers, type 2 diabetes, and mortality in the prospective NutriNet-Santé cohort. American Journal of Clinical Nutrition. 2020;112(1):195-207. | Intervention or Exposure
432 | Peacock L, Seed PT, Dalrymple KV, White SL, Poston L, Flynn AC. The UK Pregnancies Better Eating and Activity Trial (UPBEAT); Pregnancy Outcomes and Health Behaviours by Obesity Class. Int J Environ Res Public Health. Jun 30 2020;17(13) | Intervention or Exposure
433 | Peng S, Yu Y, Yu X, et al. Adherence to the Chinese dietary guidelines and metabolic syndrome among children aged 6-14 years. 13(19) | Study Design,
434 | Perraud E, Wang J, Salomé M, Huneau JF, Lapidus N, Mariotti F. Plant and Animal Protein Intakes Largely Explain the Nutritional Quality and Health Value of Diets Higher in Plants: A Path Analysis in French Adults. 9 | Outcome
435 | Petersen JM, Naimi AI, Kirkpatrick SI, Bodnar LM. Equal Weighting of the Healthy Eating Index-2010 Components May not be Appropriate for Pregnancy. | Intervention or Exposure, Outcome
436 | Petersen KS, Murphy J, Whitbread J, Clifton PM, Keogh JB. The Effect of a Peanut-Enriched Weight Loss Diet Compared to a Low-Fat Weight Loss Diet on Body Weight, Blood Pressure, and Glycemic Control: A Randomized Controlled Trial. 14(14) | Intervention or Exposure
437 | Petroni ML, Barbanti FA, Bonadonna R, et al. Dysfunctional eating in type 2 diabetes mellitus: A multicenter Italian study of socio-demographic and clinical associations. Article. Nutrition, Metabolism and Cardiovascular Diseases. 2019;29(9):983-990. | Study Design, Intervention or Exposure, Health Status, Outcome
438 | Petry CJ, Ong KK, Hughes IA, Acerini CL, Dunger DB. Temporal Trends in Maternal Food Intake Frequencies and Associations with Gestational Diabetes: The Cambridge Baby Growth Study. Nutrients. 2019;11(11):2822. | Intervention or Exposure
439 | Phillips Q. REDUCED-CARBOHYDRATE, HIGH-PROTEIN DIET SHOWS BENEFITS IN TYPE 2. Diabetes Self-Management. Fall2021 2021;38(3):14-14. | Publication Status
440 | Pintó X, Fanlo-Maresma M, Corbella E, et al. A Mediterranean Diet Rich in Extra-Virgin Olive Oil Is Associated with a Reduced Prevalence of Nonalcoholic Fatty Liver Disease in Older Individuals at High Cardiovascular Risk. Article. Journal of Nutrition. 2019;149(11):1920-1929. doi:10.1093/jn/nxz147 | Intervention or Exposure, Comparator
441 | Piovesan CH, Gustavo A, Macagnan FE, et al. The Effect of Different Interventions for Lifestyle Modifications on the Number of Diagnostic Criteria and Clinical Aspects of Metabolic Syndrome. 19(1) | Intervention or Exposure
442 | Pletsch-Borba L, Wernicke C, Meyer N, et al. A 36-month high-protein and high-unsaturated fatty-acid dietary intervention improves HbA1c in subjects aged 50-80y: preliminary results of the NutriAct Trial. Journal article; Conference proceeding. Diabetologia. 2022;65:S274–. | Publication Status
443 | Podboi ICR, Stephenson S, Pilic L, Graham CA, King A, Mavrommatis Y. Dietary Intake and TCF7L2 rs7903146 T Allele Are Associated with Elevated Blood Glucose Levels in Healthy Individuals. | Intervention or Exposure
444 | Pokharel P, Kyrø C, Olsen A, et al. Vegetable, But Not Potato, Intake is Associated With a Lower Risk of Type 2 Diabetes in the Danish Diet, Cancer and Health Cohort. | Intervention or Exposure
445 | Popp CJ, Hu L, Kharmats AY, et al. Effect of a Personalized Diet to Reduce Postprandial Glycemic Response vs a Low-fat Diet on Weight Loss in Adults With Abnormal Glucose Metabolism and Obesity: A Randomized Clinical Trial. 5(9) | Intervention or Exposure, Outcome
446 | Porter Starr KN, Connelly MA, Orenduff MC, et al. Impact on cardiometabolic risk of a weight loss intervention with higher protein from lean red meat: Combined results of 2 randomized controlled trials in obese middle-aged and older adults. Article. Journal of Clinical Lipidology. 2019;13(6):920-931. | Intervention or Exposure
447 | Prater MC, Scheurell AR, Paton CM, Cooper JA. Comparison of Blood Lipid Responses to Diets Enriched with Cottonseed Oil vs. Olive Oil in Adults with High Cholesterol in a Randomized Trial. | Study Duration
448 | Primo Martín D, Izaola Jáuregui O, López Gómez JJ, et al. Effect of a Mediterranean-pattern diet on the metabolic response secondary to weight loss; role of the single nucleotide polymorphism (rs16147) of neuropeptide Y. Journal Article; Randomized Controlled Trial. Nutricion hospitalaria. 2020;37(4):742–749. | Publication Language
449 | Primo D, Izaola O, Lopez JJ, De Luis DA. Brain derived neurotrophic factor (BDNF) polymorphism rs 10767664 affects metabolic parameters after weight loss secondary to high-fat hypocaloric diet with Mediterranean pattern. Article. European Review for Medical and Pharmacological Sciences. 2021;25(4):1944-1953. doi:10.26355/eurrev_202102_25094 | Intervention or Exposure, Comparator
450 | Qiao T, Chen Y, Duan R, et al. Beyond protein intake: does dietary fat intake in the year preceding pregnancy and during pregnancy have an impact on gestational diabetes mellitus? European Journal of Nutrition. 2021;60(6):3461-3472. | Intervention or Exposure
451 | Quattrini S, Pampaloni B, Cianferotti L, et al. Mediterranean diet adherence and dietary calcium intake in a group of pregnant women: Results of an Italian survey. Food Sci Nutr. Jul 2021;9(7):3426-3435. | Confounders
452 | Rabbani B, Chiti H, Sharifi F, Mazloomzadeh S. Effect of lifestyle modification for two years on obesity and metabolic syndrome components in elementary students: A community- based trial. 13(3) | Intervention or Exposure
453 | Raben A, Vestentoft PS, Brand-Miller J, et al. The PREVIEW intervention study: Results from a 3-year randomized 2 x 2 factorial multinational trial investigating the role of protein, glycaemic index and physical activity for prevention of type 2 diabetes. Article. Diabetes, Obesity and Metabolism. 2021;23(2):324-337. | Intervention or Exposure
454 | Rai SK, Gortmaker SL, Hu FB, et al. A South Asian Mediterranean-style diet is associated with favorable adiposity measures and lower diabetes risk: The MASALA cohort. 31(6) | Size of Study Groups
455 | Ramesh G, Wood AC, Allison MA, et al. Associations between adherence to the dietary approaches to stop hypertension (DASH) diet and six glucose homeostasis traits in the Microbiome and Insulin Longitudinal Evaluation Study (MILES). | Study Design
456 | Ramezan M, Asghari G, Mirmiran P, Tahmasebinejad Z, Azizi F. Mediterranean dietary patterns and risk of type 2 diabetes in the Islamic Republic of Iran. East Mediterr Health J. Dec 29 2019;25(12):896-904. | Size of Study Groups
457 | Ramírez-Manent JI, Altisench Jané B, Tomás Salvà M, Arroyo Bote S, González San Miguel HM, López-González Á A. Influence of Educational Level and Healthy Habits on the Prevalence of Diabesity in a Spanish Working Population. 14(19) | Study Design, Intervention or Exposure
458 | Ramos-Levi A, Barabash A, Valerio J, et al. Genetic variants for prediction of gestational diabetes mellitus and modulation of susceptibility by a nutritional intervention based on a Mediterranean diet. 13 | Intervention or Exposure
459 | Rea K, Jadallah J, Nadpara P, Goode JV. Evaluation of the impact of a community-based, pharmacist-led weight loss program focused on a high-protein diet on risk factors for cardiovascular disease. Article. Journal of the American Pharmacists Association. 2021;61(4):S147-S153. doi:10.1016/j.japh.2021.01.027 | Study Design, Intervention or Exposure
460 | Rebouillat P, Vidal R, Cravedi JP, et al. Prospective association between dietary pesticide exposure profiles and type 2 diabetes risk in the NutriNet-Santé cohort. 21(1) | Intervention or Exposure
461 | Redman LM, Drews KL, Klein S, et al. Attenuated early pregnancy weight gain by prenatal lifestyle interventions does not prevent gestational diabetes in the LIFE-Moms consortium. Article. Diabetes Research and Clinical Practice. 2021;171doi:10.1016/j.diabres.2020.108549 | Intervention or Exposure
462 | Reyes-López MA, González-Leyva CP, Rodríguez-Cano AM, et al. Diet quality is associated with a high newborn size and reduction in the risk of low birth weight and small for gestational age in a group of mexican pregnant women: An observational study. Article. Nutrients. 2021;13(6)doi:10.3390/nu13061853 | Study Design
463 | Riddle J. Plant-Based Eating and Diabetes. Today’s Dietitian. 2022;24(8):6-6. | Publication Status
464 | Rinott E, Youngster I, Yaskolka Meir A, et al. Effects of Diet-Modulated Autologous Fecal Microbiota Transplantation on Weight Regain. Gastroenterology. Jan 2021;160(1):158-173 e10. | Intervention or Exposure
465 | Riseberg E, Lopez-Cepero A, Mangano KM, Tucker KL, Mattei J. Specific Dietary Protein Sources Are Associated with Cardiometabolic Risk Factors in the Boston Puerto Rican Health Study. Article. Journal of the Academy of Nutrition and Dietetics. 2022;122(2):298-308. doi:10.1016/j.jand.2021.05.020 | Intervention or Exposure
466 | Rodrigues CCR, Riboldi BP, Rodrigues TC, et al. 304-OR: Association of Eating Patterns and Diabetic Kidney Disease in Type 2 Diabetes. Diabetes. 2021;70:N.PAG-N.PAG. | Publication Status
467 | Röhling M, Kempf K, Banzer W, et al. Prediabetes conversion to normoglycemia is superior adding a low-carbohydrate and energy deficit formula diet to lifestyle intervention— a 12-month subanalysis of the acoorh trial. Article. Nutrients. 2020;12(7):1-13. | Intervention or Exposure
468 | Röhling M, Martin K, Ellinger S, Schreiber M, Martin S, Kempf K. Weight reduction by the low-insulin-method— a randomized controlled trial. Article. Nutrients. 2020;12(10):1-17. | Intervention or Exposure
469 | Rollo ME, Baldwin JN, Hutchesson M, et al. The Feasibility and Preliminary Efficacy of an eHealth Lifestyle Program in Women with Recent Gestational Diabetes Mellitus: A Pilot Study. Int J Environ Res Public Health. Sep 28 2020;17(19) | Intervention or Exposure, Comparator
470 | Roncero-Ramos I, Alcala-Diaz JF, Rangel-Zuniga OA, et al. Prediabetes diagnosis criteria, type 2 diabetes risk and dietary modulation: The CORDIOPREV study. Clin Nutr. Feb 2020;39(2):492-500. | Intervention or Exposure, Health Status
471 | Rosas LG, Lv N, Xiao L, et al. Effect of a Culturally Adapted Behavioral Intervention for Latino Adults on Weight Loss Over 2 Years: A Randomized Clinical Trial. JAMA Netw Open. Dec 1 2020;3(12):e2027744. | Intervention or Exposure
472 | Rosenberg L, Robles YP, Li S, Ruiz-Narvaez EA, Palmer JR. A prospective study of yogurt and other dairy consumption in relation to incidence of type 2 diabetes among black women in the USA. Am J Clin Nutr. Sep 1 2020;112(3):512-518. | Intervention or Exposure
473 | Rostgaard-Hansen AL, Lau CJ, Halkjær J, Olsen A, Toft U. An updated validation of the Dietary Quality Score: associations with risk factors for cardiometabolic diseases in a Danish population. | Study Design
474 | Ru Y, Wang N, Min Y, et al. Characterization of dietary patterns and assessment of their relationships with metabolomic profiles: A community-based study. 40(5) | Study Design
475 | Rydhög B, Granfeldt Y, Frassetto L, Fontes-Villalba M, Carrera-Bastos P, Jönsson T. Assessing compliance with Paleolithic diet by calculating Paleolithic Diet Fraction as the fraction of intake from Paleolithic food groups. Article. Clinical Nutrition Experimental. 2019;25:29-35. | Health Status
476 | Sadeghian M, Hosseini SA, Zare Javid A, Ahmadi Angali K, Mashkournia A. Effect of Fasting-Mimicking Diet or Continuous Energy Restriction on Weight Loss, Body Composition, and Appetite-Regulating Hormones Among Metabolically Healthy Women with Obesity: a Randomized Controlled, Parallel Trial. Obes Surg. May 2021;31(5):2030-2039. | Intervention or Exposure, Study Duration
477 | Sadiya A, Jakapure V, Shaar G, Adnan R, Tesfa Y. Lifestyle intervention in early pregnancy can prevent gestational diabetes in highrisk pregnant women in the UAE: a randomized controlled trial. 22(1) | Intervention or Exposure, Comparator
478 | Said MS, El Sayed IT, Ibrahim EE, Khafagy GM. Effect of DASH Diet Versus Healthy Dietary Advice on the Estimated Atherosclerotic Cardiovascular Disease Risk. J Prim Care Community Health. Jan-Dec 2021;12:2150132720980952. | Intervention or Exposure, Comparator
479 | Saidj S, Ruchat SM, Henderson M, Drapeau V, Mathieu ME. Which healthy lifestyle habits mitigate the risk of obesity and cardiometabolic risk factors in Caucasian children exposed to in utero adverse gestational factors? Nutr Metab Cardiovasc Dis. Jan 4 2021;31(1):286-296. | Intervention or Exposure, Outcome
480 | Sakurai M, Ishizaki M, Morikawa Y, et al. Frequency of consumption of balanced meals, bodyweight gain and incident risk of glucose intolerance in Japanese men and women: A cohort study. 12(5) | Intervention or Exposure
481 | Salas-Salvadó J, Díaz-López A, Ruiz-Canela M, et al. Effect of a lifestyle intervention program with energy-restricted Mediterranean diet and exercise on weight loss and cardiovascular risk factors: One-year results of the PREDIMED-Plus trial. Article. Diabetes Care. 2019;42(5):777-788. | Intervention or Exposure, Comparator
482 | Sandborg J, Soderstrom E, Henriksson P, et al. Effectiveness of a Smartphone App to Promote Healthy Weight Gain, Diet, and Physical Activity During Pregnancy (HealthyMoms): Randomized Controlled Trial. JMIR Mhealth Uhealth. Mar 11 2021;9(3):e26091. | Intervention or Exposure, Outcome
483 | Santos KD, Rosado EL, Fonseca ACP, et al. FTO and ADRB2 Genetic Polymorphisms Are Risk Factors for Earlier Excessive Gestational Weight Gain in Pregnant Women with Pregestational Diabetes Mellitus: Results of a Randomized Nutrigenetic Trial. 14(5) | Health Status
484 | Santos ASAC, Rodrigues APS, Rosa LPS, Noll M, Silveira EA. Traditional Brazilian diet and olive oil reduce cardiometabolic risk factors in severely obese individuals: A randomized trial. Article. Nutrients. 2020;12(5) | Intervention or Exposure
485 | Šarac J, Havaš Auguštin D, Lovrić M, et al. A Generation Shift in Mediterranean Diet Adherence and Its Association with Biological Markers and Health in Dalmatia, Croatia. Nutrients. 2021;13(12):4564-4564. | Study Design
486 | Saslow LR, Jones LM, Sen A, et al. Comparing Very Low-Carbohydrate vs DASH Diets for Overweight or Obese Adults With Hypertension and Prediabetes or Type 2 Diabetes: A Randomized Trial. 21(3) | Intervention or Exposure, Size of Study Groups
487 | Sayón-Orea C, Razquin C, Bulló M, et al. Effect of a Nutritional and Behavioral Intervention on Energy-Reduced Mediterranean Diet Adherence Among Patients With Metabolic Syndrome: interim Analysis of the PREDIMED-Plus Randomized Clinical Trial. Comparative Study; Journal Article; Multicenter Study; Randomized Controlled Trial; Research Support, Non-U.S. Gov’t. JAMA. 2019;322(15):1486-1499. | Intervention or Exposure, Outcome
488 | Schembre SM, Jospe MR, Giles ED, et al. A low-glucose eating pattern improves biomarkers of postmenopausal breast cancer risk: An exploratory secondary analysis of a randomized feasibility trial. Article. Nutrients. 2021;13(12)doi:10.3390/nu13124508 | Intervention or Exposure, Outcome
489 | Schmidt KA, Cromer G, Burhans MS, et al. The impact of diets rich in low-fat or full-fat dairy on glucose tolerance and its determinants: a randomized controlled trial. American Journal of Clinical Nutrition. 2021;113(3):534-547. | Intervention or Exposure
490 | Schnermann ME, Schulz CA, Herder C, Alexy U, Nöthlings U. A lifestyle pattern during adolescence is associated with cardiovascular risk markers in young adults: Results from the DONALD cohort study. Article. Journal of Nutritional Science. 2021;10doi:10.1017/jns.2021.84 | Intervention or Exposure, Comparator
491 | Schroder H, Zomeno MD, Martinez-Gonzalez MA, et al. Validity of the energy-restricted Mediterranean Diet Adherence Screener. Clin Nutr. Aug 2021;40(8):4971-4979. | Outcome
492 | Schutte S, Esser D, Siebelink E, et al. Diverging metabolic effects of 2 energy-restricted diets differing in nutrient quality: a 12-week randomized controlled trial in subjects with abdominal obesity. American Journal of Clinical Nutrition. 2022;116(1):132-150. | Intervention or Exposure
493 | Scott E, Shehata M, Panesar A, Summers C, Dale J. The Low Carb Program for people with type 2 diabetes and pre-diabetes: a mixed methods feasibility study of signposting from general practice. Article. BJGP Open. 2022;6(1):1-10. doi:10.3399/BJGPO.2021.0137 | Study Design, Intervention or Exposure
494 | Seah JYH, Koh W-P, Yuan J-M, van Dam RM. Rice intake and risk of type 2 diabetes: the Singapore Chinese Health Study. European Journal of Nutrition. 2019;58(8):3349-3360. | Intervention or Exposure
495 | Seguin R, Folta S, Marshall G, Graham M, Strogatz DS. The effect of a community-based healthy lifestyle behavior change program on simple 7 score among rural women. Journal: Conference Abstract. Circulation. 2019;139 | Intervention or Exposure, Publication Status
496 | Seguin-Fowler RA, Strogatz D, Graham ML, et al. The Strong Hearts, Healthy Communities Program 2.0: An RCT Examining Effects on Simple 7. Am J Prev Med. Jul 2020;59(1):32-40. | Intervention or Exposure, Outcome
497 | Seixas MB, Pereira DAG, Ghisi GLM, et al. Exercise and Lifestyle Education program for Brazilians living with prediabetes and diabetes: A pilot randomized trial. 16(10) | Intervention or Exposure
498 | Seral-Cortes M, Sabroso-Lasa S, De Miguel-Etayo P, et al. Interaction Effect of the Mediterranean Diet and an Obesity Genetic Risk Score on Adiposity and Metabolic Syndrome in Adolescents: The HELENA Study. Nutrients. Dec 16 2020;12(12) | Study Design
499 | Seremet Kurklu N, Karatas Torun N, Ozen Kucukcetin I, Akyol A. Is there a relationship between the dietary inflammatory index and metabolic syndrome among adolescents? J Pediatr Endocrinol Metab. Apr 28 2020;33(4):495-502. | Study Design, Intervention or Exposure
500 | Shahinfar H, Amini MR, Payandeh N, et al. The link between plant-based diet indices with biochemical markers of bone turn over, inflammation, and insulin in Iranian older adults. Food Sci Nutr. Jun 2021;9(6):3000-3014. | Study Design,
501 | Shakeri Z, Mirmiran P, Khalili-Moghadam S, Hosseini-Esfahani F, Ataie-Jafari A, Azizi F. Empirical dietary inflammatory pattern and risk of metabolic syndrome and its components: Tehran Lipid and Glucose Study. Article. Diabetology and Metabolic Syndrome. 2019;11(1) | Outcome
502 | Shang X, Li Y, Xu H, et al. Leading dietary determinants identified using machine learning techniques and a healthy diet score for changes in cardiometabolic risk factors in children: a longitudinal analysis. 19(1) | Country
503 | Shang X, Li Y, Xu H, et al. Effect of multidimensional lifestyle interventions on metabolic risk reduction in children: a cluster randomised controlled trial. Journal: Article. Preventive medicine. 2020;133 | Intervention or Exposure
504 | Shang X, Li Y, Xu H, et al. Meal patterns and changes in cardiometabolic risk factors in children: a longitudinal analysis. Journal: Article. Nutrients. 2020;12(3) | Intervention or Exposure
505 | Shang X, Li Y, Xu H, Zhang Q, Liu A, Ma G. The Clustering of Low Diet Quality, Low Physical Fitness, and Unhealthy Sleep Pattern and Its Association with Changes in Cardiometabolic Risk Factors in Children. Nutrients. Feb 24 2020;12(2) | Intervention or Exposure, Country
506 | Shemirani F, Djafarian K, Fotouhi A, et al. Effect of Paleolithic-based low-carbohydrate vs. moderate-carbohydrate diets with portion-control and calorie-counting on CTRP6, asprosin and metabolic markers in adults with metabolic syndrome: A randomized clinical trial. Article. Clinical Nutrition ESPEN. 2022;48:87-98. doi:10.1016/j.clnesp.2021.11.013 | Study Duration
507 | Shen QM, Li HL, Li ZY, et al. Joint impact of BMI, physical activity and diet on type 2 diabetes: findings from two population-based cohorts in China. | Country
508 | Shen XM, Huang YQ, Zhang XY, Tong XQ, Zheng PF, Shu L. Association between dietary patterns and prediabetes risk in a middle-aged Chinese population. Journal NR. 19(1) | Study Design
509 | Shen XM, Shu L, Huang YQ, Zhang XY, Zheng PF, Zhu Q. Association between dietary patterns and glycemic control in a middle-aged Chinese population. Journal NR. Doi NR. | Study Design; Duplicate
510 | Shen X-M, Shu L, Huang Y-Q, Zhang X-Y, Zheng P-F, Zhu Q. Association between dietary patterns and glycaemic control in a middleaged Chinese population. Public Health Nutrition. 2022;25(8):2197-2205. | Study Design
511 | Shi J, Fang H, Guo Q, et al. Association of Dietary Patterns with Metabolic Syndrome in Chinese Children and Adolescents Aged 7-17: The China National Nutrition and Health Surveillance of Children and Lactating Mothers in 2016-2017. 14(17) | Study Design
512 | Shin J, Zhou X, Tan JTM, Hyppönen E, Benyamin B, Lee SH. Lifestyle Modifies the Diabetes-Related Metabolic Risk, Conditional on Individual Genetic Differences. 13 | Intervention or Exposure
513 | Shin D, Lee KW. Dietary carbohydrates interacts with AMY1 polymorphisms to influence the incidence of type 2 diabetes in Korean adults. Article. Scientific reports. 2021;11(1):16788. doi:10.1038/s41598-021-96257-z | Intervention or Exposure
514 | Shin Y, Kim Y. Psychological Stress Accompanied by a Low-Variety Diet Is Positively Associated with Type 2 Diabetes in Middle-Aged Adults. Nutrients. Aug 27 2020;12(9) | Study Design, Intervention or Exposure
515 | Shivappa N, Hebert JR, Akhoundan M, Mirmiran P, Rashidkhani B. Association between inflammatory potential of diet and odds of gestational diabetes mellitus among Iranian women. J Matern Fetal Neonatal Med. Nov 2019;32(21):3552-3558. | Study Design
516 | Singer J, Putulik Kidlapik C, Martin B, Dean HJ, Trepman E, Embil JM. Food consumption, obesity and abnormal glycaemic control in a Canadian Inuit community. Article. Clinical Obesity. 2014;4(6):316-323. doi:10.1111/cob.12074 | Study Design
517 | Siregar DAS, Rianda D, Irwinda R, et al. Associations between diet quality, blood pressure, and glucose levels among pregnant women in the Asian megacity of Jakarta. PLoS One. 2020;15(11):e0242150. | Study Design
518 | Skelly LE, Barbour-Tuck EN, Kurgan N, et al. Neutral Effect of Increased Dairy Product Intake, as Part of a Lifestyle Modification Program, on Cardiometabolic Health in Adolescent Girls With Overweight/Obesity: A Secondary Analysis From a Randomized Controlled Trial. Front Nutr. 2021;8:673589. | Intervention or Exposure
519 | Skurk T, Bosy-Westphal A, Grünerbel A, et al. Dietary recommendations for persons with type 2 diabetes mellitus. | Study Design, Health Status, Publication Status
520 | Slomski A. Low-Carbohydrate, High-Fat Diet Improved Type 2 Diabetes Without Restricting Calories. 329(4) | Publication Status
521 | Sluijs I, Van Der Schouw YT, Van Der A DL, et al. Carbohydrate quantity and quality and risk of type 2 diabetes in the European Prospective Investigation into Cancer and Nutrition-Netherlands (EPIC-NL) study. Article. American Journal of Clinical Nutrition. 2010;92(4):905-911. doi:10.3945/ajcn.2010.29620 | Intervention or Exposure
522 | Smith PJ, Mabe SM, Sherwood A, et al. Metabolic and Neurocognitive Changes Following Lifestyle Modification: Examination of Biomarkers from the ENLIGHTEN Randomized Clinical Trial. J Alzheimers Dis. 2020;77(4):1793-1803. | Intervention or Exposure
523 | Sobiecki JG, Imamura F, Davis CR, et al. A nutritional biomarker score of the Mediterranean diet and incident type 2 diabetes: Integrated analysis of data from the MedLey randomised controlled trial and the EPIC-InterAct case-cohort study. 20(4) | Intervention or Exposure, Outcome
524 | Soldevila-Domenech N, Pastor A, Sala-Vila A, et al. Sex differences in endocannabinoids during 3 years of Mediterranean diet intervention: Association with insulin resistance and weight loss in a population with metabolic syndrome. 9 | Intervention or Exposure
525 | Soltani S, Aminianfar A, Hajianfar H, Azadbakht L, Shahshahan Z, Esmaillzadeh A. Association between dietary inflammatory potential and risk of developing gestational diabetes: a prospective cohort study. 20(1) | Intervention or Exposure
526 | Song YM, Lee K. Genetic and environmental associations between insulin resistance and weight-related traits and future weight change. Nutrition. Nov - Dec 2020;79-80:110939. | Intervention or Exposure
527 | Soria-Contreras DC, Rifas-Shiman SL, Aris IM, et al. Weight Trajectories After Delivery are Associated with Adiposity and Cardiometabolic Markers at 3 Years Postpartum Among Women in Project Viva. J Nutr. Jul 1 2020;150(7):1889-1898. | Intervention or Exposure
528 | Sotos-Prieto M, Ortolá R, Ruiz-Canela M, et al. Association between the Mediterranean lifestyle, metabolic syndrome and mortality: a whole-country cohort in Spain. 20(1) | Intervention or Exposure, Comparator
529 | Steele CC, Steele TJ, Gwinner M, Rosenkranz SK, Kirkpatrick K. The relationship between dietary fat intake, impulsive choice, and metabolic health. Article. Appetite. 2021;165 | Intervention or Exposure, Study Duration,
530 | Stentz FB, Mikhael A, Kineish O, Christman J, Sands C. High protein diet leads to prediabetes remission and positive changes in incretins and cardiovascular risk factors. Article. Nutrition, Metabolism and Cardiovascular Diseases. 2021;31(4):1227-1237. | Intervention or Exposure
531 | Storz MA. Reduced Diabetes Medication Needs With a Plant-Based Diet. J Am Coll Nutr. Aug 2020;39(6):574-577. | Study Design, Publication Status
532 | Strączek K, Horodnicka-Józwa A, Szmit-Domagalska J, et al. Familial dietary intervention in children with excess body weight and its impact on eating habits, anthropometric and biochemical parameters. Article. Frontiers in Endocrinology. 2022;13doi:10.3389/fendo.2022.1034148 | Intervention or Exposure
533 | Stratakis N, Siskos AP, Papadopoulou E, et al. Urinary metabolic biomarkers of diet quality in European children are associated with metabolic health. 11 | Study Design, Outcome
534 | Sugihiro T, Yoneda M, Ohno H, Oki K, Hattori N. Associations of nutrient intakes with obesity and diabetes mellitus in the longitudinal medical surveys of Japanese Americans. Article. Journal of Diabetes Investigation. 2019;10(5):1229-1236. | Intervention or Exposure
535 | Suliga E, Brola W, Sobaś K, et al. Dietary Patterns and Metabolic Disorders in Polish Adults with Multiple Sclerosis. Nutrients. 2022;14(9):1927-1927. | Study Design, Health Status
536 | Sun Y, Chen S, Zhao X, et al. Adherence to the Dietary Approaches to Stop Hypertension diet and non-alcoholic fatty liver disease. | Study Design, Country
537 | Sun J, Ruan Y, Xu N, et al. The effect of dietary carbohydrate and calorie restriction on weight and metabolic health in overweight/obese individuals: a multi-center randomized controlled trial. Article. BMC Medicine. 2023;21(1)doi:10.1186/s12916-023-02869-9 | Intervention or Exposure
538 | Taheri E, Bostick RM, Hatami B, et al. Dietary and Lifestyle Inflammation Scores Are Inversely Associated with Metabolic-Associated Fatty Liver Disease among Iranian Adults: A Nested Case-Control Study. 152(2) | Outcome
539 | Tang N, Wu Y, Chen Y, et al. Association between postpartum low-carbohydrate-diet scores and glucose levels in Chinese women. Nutrition. Sep 2021;89:111305. | Intervention or Exposure
540 | Tanner H, Barrett HL, Callaway LK, Wilkinson SA, Nitert MD. Consumption of a low carbohydrate diet in overweight or obese pregnant women is associated with longer gestation of pregnancy. Article. Nutrients. 2021;13(10)doi:10.3390/nu13103511 | Intervention or Exposure
541 | Taylor R, Rollo ME, Baldwin JN, et al. Evaluation of a Type 2 diabetes risk reduction online program for women with recent gestational diabetes: a randomised trial. 19(1) | Intervention or Exposure, Comparator
542 | Terschüren C, Damerau L, Petersen EL, Harth V, Augustin M, Zyriax BC. Association of Dietary Pattern, Lifestyle and Chronotype with Metabolic Syndrome in Elderly-Lessons from the Population-Based Hamburg City Health Study. 19(1) | Study Design, Outcome
543 | Tettamanzi F, Bagnardi V, Louca P, et al. A high protein diet is more effective in improving insulin resistance and glycemic variability compared to a mediterranean diet—a cross-over controlled inpatient dietary study. Article. Nutrients. 2021;13(12)doi:10.3390/nu13124380 | Study Duration
544 | Teymoori F, Mokhtari E, Farhadnejad H, Mirmiran P, Rad HA, Azizi F. The dietary and lifestyle indices of insulin resistance are associated with increased risk of cardiovascular diseases: A prospective study among an Iranian adult population. | Intervention or Exposure, Outcome
545 | Teymoori F, Mokhtari E, Salehi P, Hosseini-Esfahani F, Mirmiran P, Azizi F. A nutrient pattern characterized by vitamin A, C, B6, potassium, and fructose is associated with reduced risk of insulin-related disorders: A prospective study among participants of Tehran lipid and glucose study. Diabetol Metab Syndr. Jan 26 2021;13(1):12. | Intervention or Exposure
546 | Thao U, Lajous M, Laouali N, Severi G, Boutron-Ruault MC, MacDonald CJ. Replacing processed red meat with alternative protein sources is associated with a reduced risk of hypertension and diabetes in a prospective cohort of French women. Article in Press. The British journal of nutrition. 2022:1-31. doi:10.1017/S0007114522002689 | Intervention or Exposure, Comparator
547 | Thomas MS, Puglisi M, Malysheva O, et al. Eggs Improve Plasma Biomarkers in Patients with Metabolic Syndrome Following a Plant-Based Diet-A Randomized Crossover Study. 14(10) | Intervention or Exposure, Study Duration
548 | Titcomb TJ, Liu B, Wahls TL, et al. Comparison of the ketogenic ratio of macronutrients with the low-carbohydrate diet score and their association with risk of type 2 diabetes in postmenopausal women: A secondary analysis of the women’s health initiative. | Intervention or Exposure
549 | Tomaino L, Reyes Suarez D, Reyes Dominguez A, Garcia Cruz LM, Ramos Diaz M, Serra Majem L. Adherence to Mediterranean diet is not associated with birthweight - Results form a sample of Canarian pregnant women. Nutr Hosp. Feb 17 2020;37(1):86-92. La adherencia a la dieta mediterranea no se asocia al peso al nacer: resultados de una muestra de mujeres canarias embarazadas. | Study Design, Outcome
550 | Tosi M, Matelloni IA, Mancini M, et al. Multiple beneficial effects of 1-year nutritional-behavioral intervention on anthropometric and metabolic parameters in overweight and obese boys. | Study Design, Intervention or Exposure
551 | Tresserra-Rimbau A, Castro-Barquero S, Becerra-Tomás N, et al. Adopting a High-Polyphenolic Diet Is Associated with an Improved Glucose Profile: Prospective Analysis within the PREDIMED-Plus Trial. 11(2) | Intervention or Exposure
552 | Trimigno A, Khakimov B, Savorani F, et al. Human urine (1)H NMR metabolomics reveals alterations of protein and carbohydrate metabolism when comparing habitual Average Danish diet vs. healthy New Nordic diet. Nutrition. Nov - Dec 2020;79-80:110867. | Outcome
553 | Trouwborst I, Gijbels A, Jardon KM, et al. Cardiometabolic health improvements upon dietary intervention are driven by tissue-specific insulin resistance phenotype: A precision nutrition trial. Article. Cell Metabolism. 2023;35(1):71-83.e5. doi:10.1016/j.cmet.2022.12.002 | Intervention or Exposure
554 | Tryggvadottir EA, Halldorsson TI, Landberg R, et al. Higher Alkylresorcinol Concentrations, a Consequence of Whole-Grain Intake, are Inversely Associated with Gestational Diabetes Mellitus in Iceland. Article. The Journal of nutrition. 2021;151(5):1159-1166. doi:10.1093/jn/nxaa449 | Intervention or Exposure
555 | Tryggvadottir EA, Gunnarsdottir I, Birgisdottir BE, et al. Early pregnancy plasma fatty acid profiles of women later diagnosed with gestational diabetes. BMJ Open Diabetes Res Care. Aug 2021;9(1) | Intervention or Exposure
556 | Tsaban G, Yaskolka Meir A, Rinott E, et al. The effect of green Mediterranean diet on cardiometabolic risk; a randomised controlled trial. Heart. Nov 23 2020; | Intervention or Exposure, Comparator
557 | Tsai TJ, Li MC. Adherence to the Taiwan Daily Food Guide and the Risk of Type 2 Diabetes: A Populational Study in Taiwan. 20(3) | Study Design
558 | Tunçer E, Keser A, Ünsal EN, Güneş SO, Akın O. The Correlation Between Adherence to Mediterranean Diet and HOMA-IR in Children and Adolescents. Article. Çocuk ve Adölesanlarda Akdeniz Diyetine Uyum ile HOMA-IR Arasındaki İlişki. 2022;20(2):188-196. doi:10.4274/JCP.2022.59251 | Study Design
559 | Tuomainen M, Karkkainen O, Leppanen J, et al. Quantitative assessment of betainized compounds and associations with dietary and metabolic biomarkers in the randomized study of the healthy Nordic diet (SYSDIET). Am J Clin Nutr. Nov 1 2019;110(5):1108-1118. | Intervention or Exposure, Comparator
560 | Turner-McGrievy GM, Wilson MJ, Carswell J, et al. A 12-Week Randomized Intervention Comparing the Healthy US, Mediterranean, and Vegetarian Dietary Patterns of the US Dietary Guidelines for Changes in Body Weight, Hemoglobin A1c, Blood Pressure, and Dietary Quality among African American Adults. 153(2) | Intervention or Exposure
561 | Tzenios N, Lewis ED, Crowley DC, Chahine M, Evans M. Examining the Efficacy of a Very-Low-Carbohydrate Ketogenic Diet on Cardiovascular Health in Adults with Mildly Elevated Low-Density Lipoprotein Cholesterol in an Open-Label Pilot Study. Article. Metabolic Syndrome and Related Disorders. 2022;20(2):94-103. doi:10.1089/met.2021.0042 | Study Design, Intervention or Exposure
562 | Uçar Z, Akman M. Mediterranean type diet protects adult individuals from diabetes. Article. Progress in Nutrition. 2021;23(3)doi:10.23751/pn.v23i3.10828 | Study Design
563 | Unwin D, Delon C, Unwin J, Tobin S, Taylor R. What predicts drug-free type 2 diabetes remission? Insights from an 8-year general practice service evaluation of a lower carbohydrate diet with weight loss. Article in Press. BMJ Nutrition, Prevention and Health. 2023;doi:10.1136/bmjnph-2022-000544 | Intervention or Exposure
564 | Unwin DJ, Tobin SD, Murray SW, Delon C, Brady AJ. Substantial and sustained improvements in blood pressure, weight and lipid profiles from a carbohydrate restricted diet: An observational study of insulin resistant patients in primary care. Article. International Journal of Environmental Research and Public Health. 2019;16(15) | Intervention or Exposure
565 | Ushula TW, Mamun A, Darssan D, et al. Dietary patterns explaining variations in blood biomarkers in young adults are associated with the 30-year predicted cardiovascular disease risks in midlife: A follow-up study. | Size of Study Groups, Outcome
566 | Utari A, Maududi MS, Kusumawati NRD, Mexitalia M. Effects of low glycemic index diet on insulin resistance among obese adolescent with non-alcoholic fatty liver disease: A randomized controlled trial. Article. Medical Journal of Indonesia. 2019;28(2):123-128. | Intervention or Exposure
567 | Vahid F, Hoge A, Hébert JR, Bohn T. Association of diet quality indices with serum and metabolic biomarkers in participants of the ORISCAV-LUX-2 study. | Study Design
568 | Vahid F, Goodarzi R, Shivappa N, Hébert JR, Fazeli Moghadam E. Dietary Inflammatory Index (DII®): A significant association between coronary heart disease and DII® in Armenian adults. Article. European Journal of Preventive Cardiology. 2020;27(19):2235-2237. | Outcome, Publication Status
569 | Valerio J, Barabash A, Garcia de la Torre N, et al. The Relationship between Serum Adipokines, miR-222-3p, miR-103a-3p and Glucose Regulation in Pregnancy and Two to Three Years Post-Delivery in Women with Gestational Diabetes Mellitus Adhering to Mediterranean Diet Recommendations. 14(22) | Intervention or Exposure, Comparator
570 | Valsdottir TD, Øvrebø B, Kornfeldt TM, et al. Effect of aerobic exercise and low-carbohydrate high-fat diet on glucose tolerance and android/gynoid fat in overweight/obese women: A randomized controlled trial. Article. Frontiers in Physiology. 2023;14doi:10.3389/fphys.2023.1056296 | Intervention or Exposure, Study Duration
571 | van Baak MA, Roumans NJT, Mariman ECM. Diet Composition, Glucose Homeostasis, and Weight Regain in the YoYo Study. Nutrients. Jun 30 2021;13(7) | Intervention or Exposure
572 | van de Pas KGH, Lubrecht JW, Hesselink ML, Winkens B, van Dielen FMH, Vreugdenhil ACE. The Effect of a Multidisciplinary Lifestyle Intervention on Health Parameters in Children versus Adolescents with Severe Obesity. Article. Nutrients. 2022;14(9)doi:10.3390/nu14091795 | Study Design, Intervention or Exposure
573 | van Etten S, Crielaard L, Muilwijk M, et al. Lifestyle clusters related to type 2 diabetes and diabetes risk in a multi-ethnic population: The HELIUS study. Article. Preventive Medicine. 2020;137 | Intervention or Exposure, Comparator
574 | van Poppel MNM, Jelsma JGM, Simmons D, et al. Mediators of lifestyle behaviour changes in obese pregnant women. Secondary analyses from the DALI lifestyle randomised controlled trial. Article. Nutrients. 2019;11(2) | Intervention or Exposure, Outcome
575 | Vassou C, Yannakoulia M, Georgousopoulou EN, et al. Irrational Beliefs, Dietary Habits and 10-Year Incidence of Type 2 Diabetes; the ATTICA Epidemiological Study (2002-2012). 17(1) | Size of Study Groups
576 | Velázquez-López L, Ponce-Martínez X, Colín-Ramírez E, Muñoz-Torres AV, Escobedo-de la Peña J. Un patrón dietético con alto contenido de lácteos enteros y bebidas azucaradas se asocia con la hemoglobina glicosilada y el peso en pacientes mexicanos con diabetes de tipo 2. Article in Press. A dietary pattern high in full-fat dairy and sweetened beverages is associated with glycated hemoglobin and weight in Mexican patients with type-2 diabetes. 2021;doi:10.20960/nh.03651 | Study Design, Health Status
577 | Vidal-Ostos F, Ramos-Lopez O, Jebb SA, et al. Dietary protein and the glycemic index handle insulin resistance within a nutritional program for avoiding weight regain after energy-restricted induced weight loss. Article. Nutrition and Metabolism. 2022;19(1)doi:10.1186/s12986-022-00707-y | Intervention or Exposure
578 | Vinke PC, Navis G, Kromhout D, Corpeleijn E. Associations of Diet Quality and All-Cause Mortality Across Levels of Cardiometabolic Health and Disease: A 7.6-Year Prospective Analysis From the Dutch Lifelines Cohort. 44(5) | Outcome
579 | Virtanen E, Kivela J, Wikstrom K, et al. Feel4Diabetes healthy diet score: development and evaluation of clinical validity. BMC Endocr Disord. May 6 2020;20(Suppl 2):46. | Outcome
580 | Vitale M, Calabrese I, Massimino E, et al. Dietary inflammatory index score, glucose control and cardiovascular risk factors profile in people with type 2 diabetes. Article. International journal of food sciences and nutrition. 2021;72(4):529-536. doi:10.1080/09637486.2020.1832054 | Health Status
581 | Vitale S, Mattioli V, Shivappa N, et al. The dietary inflammatory index in women diagnosed with breast cancer after 12 months of dietary. Treatment with a Mediterranean diet low in glycemic index: data from DEDICA randomized controlled trial. Nutrition, Metabolism & Cardiovascular Diseases. 2021;31(11):3256-3256. | Intervention or Exposure, Publication status
582 | Vizzari G, Sommariva MC, Cas MD, et al. Circulating salicylic acid and metabolic profile after 1-year nutritional–behavioral intervention in children with obesity. Article. Nutrients. 2019;11(5) | Study Design, Intervention or Exposure
583 | Vizzuso S, Amatruda M, Banderali G, Mameli C, Zuccotti G, Verduci E. One year individual or group based lifestyle intervention in obese. Impact on metabolic profile and body composition. Journal: Conference Abstract. Obesity reviews. 2020;21(SUPPL 1) | Study Design, Publication Status
584 | Vucic Lovrencic M, Geric M, Kosuta I, Dragicevic M, Garaj-Vrhovac V, Gajski G. Sex-specific effects of vegetarian diet on adiponectin levels and insulin sensitivity in healthy non-obese individuals. Nutrition. Nov - Dec 2020;79-80:110862. | Study Design, Intervention or Exposure
585 | Wabo TMC, Nkondjock VRN, Onwuka JU, Sun C, Han T, Sira J. Association of fourteen years diet quality trajectories and type 2 diabetes mellitus with related biomarkers. Aging (Albany NY). Mar 26 2021;13(7):10112-10127. | Country
586 | Wagner S, Lioret S, Girerd N, et al. Association of Dietary Patterns Derived Using Reduced-Rank Regression With Subclinical Cardiovascular Damage According to Generation and Sex in the STANISLAS Cohort. J Am Heart Assoc. Apr 7 2020;9(7):e013836. | Outcome
587 | Wakasugi M, Narita I, Iseki K, et al. Healthy Lifestyle and Incident Hypertension and Diabetes in Participants with and without Chronic Kidney Disease: The Japan Specific Health Checkups (J-SHC) Study. Article. Internal Medicine. 2022;61(19):2841-2851. doi:10.2169/internalmedicine.8992-21 | Intervention or Exposure
588 | Wang CR, Hu TY, Hao FB, et al. Type 2 diabetes prevention diet and all-cause and cause-specific mortality in the US population: a prospective study. | Outcome
589 | Wang DD, Qi Q, Wang Z, et al. The Gut Microbiome Modifies the Association between a Mediterranean Diet and Diabetes in US Hispanic / Latino Population. Journal of Clinical Endocrinology and Metabolism. 2022 | Study Duration; Duplicate
590 | Wang J, Lv S, Zhou Y, et al. The association between low carbohydrate diet scores and cardiometabolic risk factors in Chinese adults. | Study Design
591 | Wang J, Xie Z, Chen P, Wang Y, Li B, Dai F. Effect of dietary pattern on pregnant women with gestational diabetes mellitus and its clinical significance. 17(1) | Health Status
592 | Wang W, Lv J, Yu C, et al. Lifestyle factors and fetal and childhood origins of type 2 diabetes: A prospective study of Chinese and European adults. | Intervention or Exposure
593 | Wang Y, Chen B, Zhang J, et al. Diets with Higher Insulinemic Potential Are Associated with Increased Risk of Overall and Cardiovascular Disease-specific Mortality. Journal NR; 128(10); doi NR | Outcome; Duplicate
594 | Wang Y, Chen B, Zhang J, et al. Diets with Higher Insulinemic Potential Are Associated with Increased Risk of Overall and Cardiovascular Disease-specific Mortality. Journal NR; doi NR | Outcome; Duplicate
595 | Wang Y, Xie W, Tian T, et al. The Relationship between Dietary Patterns and High Blood Glucose among Adults Based on Structural Equation Modelling. 14(19) | Study Design
596 | Wang DD, Qi Q, Wang Z, et al. The Gut Microbiome Modifies the Association between a Mediterranean Diet and Diabetes in USA Hispanic/ Latino Population. Article. Journal of Clinical Endocrinology and Metabolism. 2022;107(3):E924-E934. doi:10.1210/clinem/dgab815 | Study Design
597 | Wang H, Wang Y, Shi Z, et al. Association between Dietary Patterns and Metabolic Syndrome and Modification Effect of Altitude: A Cohort Study of Tibetan Adults in China. Article. Nutrients. 2023;15(9)doi:10.3390/nu15092226 | Outcome
598 | Wang Z, Adair LS, Cai J, et al. Diet quality is linked to insulin resistance among adults in China. Article. Journal of Nutrition. 2017;147(11):2102-2108. doi:10.3945/jn.117.256180 | Country
599 | Watanabe M, Sianoya A, Mishima R, et al. Gut microbiome status of urban and rural Filipino adults in relation to diet and metabolic disorders. Article. FEMS microbiology letters. 2021;368(20)doi:10.1093/femsle/fnab149 | Study Design
600 | Wawro N, Pestoni G, Riedl A, et al. Association of Dietary Patterns and Type-2 Diabetes Mellitus in Metabolically Homogeneous Subgroups in the KORA FF4 Study. Nutrients. Jun 5 2020;12(6) | Study Design
601 | Weston LJ, Kim H, Talegawkar SA, Tucker KL, Correa A, Rebholz CM. Plant-based diets and incident cardiovascular disease and all-cause mortality in African Americans: A cohort study. Article. PLoS Medicine. 2022;19(1)doi:10.1371/journal.pmed.1003863 | Outcome
602 | White SL, Flynn AC, Poston L. Impact of a positive or negative diagnosis of gestational diabetes and treatment, on weight change and dietary behaviour in an obese cohort: secondary analysis of the UK pregnancies better eating and activity trial (UPBEAT) randomised controlled trial (RCT). Journal: Conference Abstract. Diabetic medicine. 2019;36:65-. | Publication Status
603 | Wilson JE, Blizzard L, Gall SL, et al. An age- and sex-specific dietary guidelines index is a valid measure of diet quality in an Australian cohort during youth and adulthood. Article. Nutrition Research. 2019;65:43-53. | Study Design,
604 | Wong JMW, Yu S, Ma C, et al. Stimulated Insulin Secretion Predicts Changes in Body Composition Following Weight Loss in Adults with High BMI. Article in Press. The Journal of nutrition. 2021;doi:10.1093/jn/nxab315 | Intervention or Exposure
605 | Wu L, Ouyang J, Lai Y, et al. Combined healthy lifestyle in early pregnancy and risk of gestational diabetes mellitus: A prospective cohort study. | Intervention or Exposure
606 | Wu SL, Peng LY, Chen YM, et al. Greater Adherence to Dietary Guidelines Associated with Reduced Risk of Cardiovascular Diseases in Chinese Patients with Type 2 Diabetes. Article. Nutrients. 2022;14(9)doi:10.3390/nu14091713 | Study Design, Health Status
607 | Wu W, Tang N, Zeng J, Jing J, Cai L. Dietary Protein Patterns during Pregnancy Are Associated with Risk of Gestational Diabetes Mellitus in Chinese Pregnant Women. Article. Nutrients. 2022;14(8)doi:10.3390/nu14081623 | Study Design, Intervention or Exposure
608 | Wu Y, Sun G, Zhou X, et al. Pregnancy dietary cholesterol intake, major dietary cholesterol sources, and the risk of gestational diabetes mellitus: A prospective cohort study. Clin Nutr. May 2020;39(5):1525-1534. | Intervention or Exposure
609 | Würtz AML, Jakobsen MU, Bertoia ML, et al. Replacing the consumption of red meat with other major dietary protein sources and risk of type 2 diabetes mellitus: A prospective cohort study. Article. American Journal of Clinical Nutrition. 2021;113(3):612-621. | Intervention or Exposure
610 | Xia Y, Cao L, Zhang Q, et al. Adherence to a vegetable dietary pattern attenuates the risk of non-alcoholic fatty liver disease on incident type 2 diabetes: the TCLSIH cohort study. | Health Status, Comparator
611 | Xiao X, Qin Z, Lv X, et al. Dietary patterns and cardiometabolic risks in diverse less-developed ethnic minority regions: results from the China Multi-Ethnic Cohort (CMEC) Study. Article. The Lancet Regional Health - Western Pacific. 2021;15doi:10.1016/j.lanwpc.2021.100252 | Study Design,
612 | Xu Y, Li Y, Liang S, Li G. Differential analysis of nutrient intake, insulin resistance and lipid profiles between healthy and premature thelarche Chinese girls. Italian Journal of Pediatrics. 2019;45(1):1-6. | Study Design, Intervention or Exposure
613 | Yabe D, Kuwata H, Fujiwara Y, et al. Dietary instructions focusing on meal-sequence and nutritional balance for prediabetes subjects: An exploratory, cluster-randomized, prospective, open-label, clinical trial. J Diabetes Complications. Dec 2019;33(12):107450. | Intervention or Exposure
614 | Yaegashi A, Kimura T, Hirata T, Iso H, Tamakoshi A. Association between low-carbohydrate diet score and incidence of type 2 diabetes among Japanese adults: The JACC Study. Article. Journal of Nutritional Science. 2023;12doi:10.1017/jns.2022.122 | Intervention or Exposure
615 | Yamada P, Paetow A, Chan M, Arslan A, Landberg R, Young BK. Pregnancy outcomes with differences in grain consumption: a randomized controlled trial. Journal of Perinatal Medicine. 2022;50(4):411-418. | Intervention or Exposure
616 | Yamada S, Inoue G, Ooyane H, Nishikawa H. Changes in body weight, dysglycemia, and dyslipidemia after moderately lowcarbohydrate diet education (Locabo challenge program) among workers in japan. Article. Diabetes, Metabolic Syndrome and Obesity: Targets and Therapy. 2021;14:2863-2870. | Study Design, Intervention or Exposure
617 | Yan F, Eshak ES, Shirai K, et al. Soy Intake and Risk of Type 2 Diabetes Among Japanese Men and Women: JACC Study. 8 | Intervention or Exposure
618 | Yang HJ, Kim MJ, Hur HJ, et al. Inverse Association of the Adequacy and Balance Scores in the Modified Healthy Eating Index with Type 2 Diabetes in Women. 15(7) | Study Design
619 | Yang J, Qian F, Chavarro JE, et al. Modifiable risk factors and long term risk of type 2 diabetes among individuals with a history of gestational diabetes mellitus: prospective cohort study. 378 | Intervention or Exposure
620 | Yang R, Lv J, Yu C, et al. Importance of healthy lifestyle factors and ideal cardiovascular health metrics for risk of heart failure in Chinese adults. Article. International Journal of Epidemiology. 2022;51(2):567-578. doi:10.1093/ije/dyab236 | Intervention or Exposure, Outcome
621 | Yang X, Li Y, Wang C, et al. Association of plant-based diet and type 2 diabetes mellitus in Chinese rural adults: The Henan Rural Cohort Study. Article. Journal of Diabetes Investigation. 2021;12(9):1569-1576. doi:10.1111/jdi.13522 | Study Design,
622 | Yashpal S, Liese AD, Boucher BA, et al. Metabolomic profiling of the Dietary Approaches to Stop Hypertension (DASH) diet provides novel insights for the nutritional epidemiology of type 2 diabetes mellitus (T2DM). | Intervention or Exposure, Outcome
623 | Yi SY, Steffen LM, Zhou X, Shikany JM, Jacobs DR, Jr. Association of nut consumption with CVD risk factors in young to middle-aged adults: The Coronary Artery Risk Development in Young Adults (CARDIA) study. | Intervention or Exposure
624 | Yilmaz S, Eskici G, Mertoglu C, Ayaz A. Effect of different protein diets on weight loss, inflammatory markers, and cardiometabolic risk factors in obese women. Article. Journal of Research in Medical Sciences. 2021;26(1)doi:10.4103/jrms.JRMS_611_20 | Study Design, Intervention or Exposure, Study Duration
625 | Yisahak SF, Hinkle SN, Mumford SL, et al. Vegetarian diets during pregnancy, and maternal and neonatal outcomes. Int J Epidemiol. Mar 3 2021;50(1):165-178. | Intervention or Exposure
626 | Yokose C, McCormick N, Rai SK, et al. Effects of Low-Fat, Mediterranean, or Low-Carbohydrate Weight Loss Diets on Serum Urate and Cardiometabolic Risk Factors: A Secondary Analysis of the Dietary Intervention Randomized Controlled Trial (DIRECT). Diabetes Care. Nov 2020;43(11):2812-2820. | Intervention or Exposure
627 | Yuan S, He J, Wu S, et al. Trends in dietary patterns over the last decade and their association with long-term mortality in general US populations with undiagnosed and diagnosed diabetes. 13(1) | Outcome
628 | Yuste Gómez A, Ramos Álvarez MDP, Bartha JL. Influence of Diet and Lifestyle on the Development of Gestational Diabetes Mellitus and on Perinatal Results. Article. Nutrients. 2022;14(14)doi:10.3390/nu14142954 | Intervention or Exposure
629 | Yuzbashian E, Pakseresht M, Vena J, Chan CB. Association of dairy consumption patterns with the incidence of type 2 diabetes: Findings from Alberta’s Tomorrow Project. Article in Press. Nutrition, Metabolism and Cardiovascular Diseases. 2022;doi:10.1016/j.numecd.2022.09.022 | Intervention or Exposure
630 | Zamani B, Milajerdi A, Tehrani H, Bellissimo N, Brett NR, Azadbakht L. Association of a plant-based dietary pattern in relation to gestational diabetes mellitus. Nutr Diet. Nov 2019;76(5):589-596. | Study Design
631 | Zhang B, Xu K, Mi B, et al. Maternal Dietary Inflammatory Potential and Offspring Birth Outcomes in a Chinese Population. 153(5) | Study Design, Intervention or Exposure
632 | Zhang N, Zhou M, Li M, Ma G. Effects of Smartphone-Based Remote Interventions on Dietary Intake, Physical Activity, Weight Control, and Related Health Benefits Among the Older Population With Overweight and Obesity in China: Randomized Controlled Trial. 25 | Intervention or Exposure
633 | Zhang X, Xiao D, Guzman G, Edirisinghe I, Burton-Freeman B. Avocado consumption for 12 weeks and cardio-metabolic risk factors: a randomized controlled trial in adults with overweight or obesity and insulin resistance. | Intervention or Exposure
634 | Zhang Y, Wang Y, Zhang S, Zhang Y, Zhang Q. Complex Association Among Diet Styles, Sleep Patterns, and Obesity in Patients with Diabetes. 16 | Study Design, Health Status
635 | Zhang Z, Tabung FK, Jin Q, et al. Diet-Driven Inflammation and Insulinemia and Risk of Interval Breast Cancer. | Outcome
636 | Zhang C, Olsen SF, Hinkle SN, et al. Diabetes & Women’s Health (DWH) Study: An observational study of long-term health consequences of gestational diabetes, their determinants and underlying mechanisms in the USA and Denmark. BMJ Open. 2019;9(4) | Intervention or Exposure
637 | Zhang S, Meng G, Zhang Q, et al. Dietary fibre intake and risk of prediabetes in China: results from the Tianjin Chronic Low-grade Systemic Inflammation and Health (TCLSIH) Cohort Study. British Journal of Nutrition. 2022;128(4):753-761. | Intervention or Exposure
638 | Zhang X, Gong Y, Della Corte K, et al. Relevance of dietary glycemic index, glycemic load and fiber intake before and during pregnancy for the risk of gestational diabetes mellitus and maternal glucose homeostasis. Clinical Nutrition. 2021;40(5):2791-2799. | Intervention or Exposure
639 | Zhang YZ, Zhou L, Tian L, et al. A mid-pregnancy risk prediction model for gestational diabetes mellitus based on the maternal status in combination with ultrasound and serological findings. Experimental and Therapeutic Medicine. 2020;20(1):293-300. | Intervention or Exposure
640 | Zhang Z, Wu Y, Zhong C, et al. Association between dietary inflammatory index and gestational diabetes mellitus risk in a prospective birth cohort study. Nutrition. Jul-Aug 2021;87-88:111193. | Intervention or Exposure
641 | Zhao R, Zhou L, Lei G, et al. Dietary Acid Load Is Positively Associated With Risk of Gestational Diabetes Mellitus in a Prospective Cohort of Chinese Pregnant Women. 9 | Intervention or Exposure
642 | Zheng C, Shi C, Bai J, Shao W, Zhang C, Bu J. Large-scale investigation on healthy status of teachers in Jiangsu Province, China. Progress in Nutrition. 2019;21(2):294-298. | Study Design
643 | Zhong H, Penders J, Shi Z, et al. Impact of early events and lifestyle on the gut microbiota and metabolic phenotypes in young school-age children. Microbiome. 2019;7(1) | Intervention or Exposure
644 | Zhou C, Liu C, Zhang Z, et al. Variety and quantity of dietary protein intake from different sources and risk of new-onset diabetes: a Nationwide Cohort Study in China. 20(1) | Intervention or Exposure
645 | Zhou C, Zhang Z, Liu M, et al. Dietary carbohydrate intake and new-onset diabetes: A nationwide cohort study in China. Article. Metabolism: Clinical and Experimental. 2021;123. doi:10.1016/j.metabol.2021.154865 | Intervention or Exposure
646 | Zhou J, Sheng J, Fan Y, Zhu X, Wang S. Dietary patterns, dietary intakes and the risk of type 2 diabetes: results from the Hefei Nutrition and Health Study. International journal of food sciences and nutrition. 2019;70(4):412-420. | Study Design,
647 | Zhou X, Chen R, Zhong C, et al. Fresh fruit intake in pregnancy and association with gestational diabetes mellitus: A prospective cohort study. Nutrition. 2019;60:129-135. | Intervention or Exposure
648 | Zhu Y. Are you what you eat? Through the lens of prepregnancy plant-based diets and risk of gestational diabetes. | Study Design, Publication Status
649 | Zhu R, Fogelholm M, Jalo E, et al. Animal-based food choice and associations with long-term weight maintenance and metabolic health after a large and rapid weight loss: The PREVIEW study. Clinical Nutrition. 2022;41(4):817-828. doi:10.1016/j.clnu.2022.02.002 | Intervention or Exposure
650 | Zhu R, Fogelholm M, Poppitt SD, et al. Adherence to a plant-based diet and consumption of specific plant foods—associations with 3-year weight-loss maintenance and cardiometabolic risk factors: A secondary analysis of the preview intervention study. Nutrients. 2021;13(11). doi:10.3390/nu13113916 | Size of Study Groups
651 | Zhu Z, Li FR, Jia Y, et al. Association of Lifestyle With Incidence of Heart Failure According to Metabolic and Genetic Risk Status: A Population-Based Prospective Study. Article in Press. Circulation Heart failure. 2022. doi:10.1161/CIRCHEARTFAILURE.122.009592 | Outcome
652 | Zhuang P, Zhang Y, Mao L, et al. The association between consumption of monounsaturated fats from animal- v. plant-based foods and the risk of type 2 diabetes: a prospective nationwide cohort study. Br J Nutr. Feb 27 2020:1-10. | Intervention or Exposure
653 | Zinn C, McPhee J, Harris N, Williden M, Prendergast K, Schofield G. A 12-week low-carbohydrate, high-fat diet improves metabolic health outcomes over a control diet in a randomised controlled trial with overweight defence force personnel. Academic Journal. Applied physiology, nutrition & metabolism. 2017;42(11):1158–1164. | Intervention or Exposure, Publication Date