# Appendix 3 Inclusion and exclusion criteria comparison between existing^*^ * Dietary Patterns Technical Expert Collaborative and NESR Staff. A Series of Systematic Reviews on the Relationship Between Dietary Patterns and Health Outcomes. March 2014. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://nesr.usda.gov/sites/default/files/2019-06/DietaryPatternsReport-FullFinal2.pdf and updated systematic reviews

Table A 3 Inclusion and exclusion criteria comparison between existing and updated systematic reviews for the research question: What is the relationship between dietary patterns consumed and risk of type 2 diabetes?

Category | Existing Review | Updated Review | Change and Rationale
Study design | [underlined: Included:]; - Randomized controlled trials; - Non-randomized controlled trials (including quasi-experimental and controlled before and after studies); - Quasi-experimental studies (i.e., prospective cohort studies); [underlined: Excluded:]; - Nested case-control studies; - Case-control studies; - Uncontrolled trials; - Case-control studies; - Cross-sectional studies; - Uncontrolled before-and-after studies; - Narrative reviews; - Systematic reviews; - Meta-analyses | [underlined: Included:]; - Randomized controlled trials; - Non-randomized controlled trials^†^; † Including quasi-experimental and controlled before-and-after studies; - Prospective cohort studies; - Retrospective cohort studies; - Nested case-control studies; [underlined: Excluded]:; - Uncontrolled trials^‡^; ‡ Including uncontrolled before-and-after studies; - Case-control studies; - Cross-sectional studies; - Ecological studies; - Narrative reviews; - Systematic reviews; - Meta-analyses; - Modeling and simulation studies; - Mendelian randomization studies | Study design criteria were modified to enable focus on the strongest body of evidence
Publication date | [underlined: Included:]; - January 1980 – August 2013; [underlined: Excluded]:; Before January 1980, after August 2013 | [underlined: Included:]; - August 2013 – May 2023^*^; * This review update date range encompasses the original systematic review date range, which included articles published from January 1980 to August 2013; [underlined: Excluded:]; Before August 2013, after May 2023 | Dates were modified to enable focus on the most recent evidence.
Population: Study participants | [underlined: Included:]; - Human; [underlined: Excluded]:; - Non-human | [underlined: Included:]; - Human; [underlined: Excluded]:; - Non-human | - No change
Population: Life stage | [underlined: Included]:; - At intervention/exposure and outcome:; - Children, adolescents, adults, and older adults aged 2 years and older; [underlined: Excluded]:; - At intervention/exposure and outcome:; - Infants and young children (birth up to 24 months) | [underlined: Included]:; - At intervention/exposure:; - Infants and young children (birth up to 24 months); - Children and adolescents (2 up to 19 year); - Adults and older adults (19 years and older); - Individuals during pregnancy; - Individuals during postpartum; [underlined: Excluded]:; - At outcome:; - Infants and young children (birth up to 24 months); - Individuals during pregnancy; - Individuals during postpartum | - No change other than formatting
Population: Health Status | [underlined: Included:]; - Subjects who were healthy or at elevated chronic disease risk; - Low-calorie intervention (defined as <1,600 kcal/day for women and <2,000 kcal/day for men); [underlined: Excluded]:; - Subjects who were hospitalized, diagnosed with disease, and/or receiving medical treatment | [underlined: Included:]; - Studies that [underlined: exclusively] enroll participants not diagnosed with a disease^*^; * Studies that enroll participants who are at risk for chronic disease were included; - Studies that enroll [underlined: some] participants:; - diagnosed with a disease;; - with severe undernutrition, failure to thrive/underweight, stunting, or wasting;; - born preterm,^†^ with low birth weight,^‡^ and/or small for gestational age;; † Gestational age <37 weeks and 0/7 days; ‡ Birth weight <2500g; - and/or with the outcome of interest; - who became pregnant using Assisted Reproductive Technologies;; - with multiple gestation pregnancies;; - pre- or post-bariatric surgery;; and/or receiving pharmacotherapy to treat obesity; [underlined: Excluded:]; - Studies that [underlined: exclusively] enroll participants:; - diagnosed with a disease;^§^; § Studies that exclusively enroll participants with obesity were included; - hospitalized for an illness, injury, or surgery;^**^; ** Studies that exclusively enroll participants post-cesarean section were included; - with severe undernutrition, failure to thrive/underweight, stunting, or wasting;; - born preterm,^†^ with low birth weight,^‡^ and/or small for gestational age; - who became pregnant using Assisted Reproductive Technologies;; - with multiple gestation pregnancies;; - pre- or post-bariatric surgery;; - and/or receiving pharmacotherapy to treat obesity | - No change other than to clarify intent
Intervention/exposure | [underlined: Included:]; - A description of the dietary pattern(s) consumed by subjects (i.e., the quantities, proportions, variety, or combination of different foods, drinks, and nutrients (when available) in diets, and the frequency with which they are habitually consumed), including, at a minimum, a description of the foods and beverages in the pattern); - Dietary patterns may be measured or derived using a variety of approaches, such as adherence to a priori patterns (indices/scores), data driven patterns (factor or cluster analysis), reduced rank regression, or other methods, including clinical trials.; [underlined: Excluded:]; - Studies that do not provide a description of the dietary pattern, which at minimum, must include the foods and beverages in the pattern (i.e., studies that examine a labeled dietary pattern, but do not describe the foods and beverages consumed). | [underlined: Included:]; - Studies that examine consumption of and/or adherence to a dietary pattern [i.e., the quantities, proportions, variety, or combination of different foods, drinks, and nutrients (when available) in diets, and the frequency with which they are habitually consumed], including, at a minimum, a description of the foods and beverages in the pattern of each intervention/exposure and comparator group; - Dietary patterns may be measured or derived using a variety of approaches, such as adherence to a priori patterns (indices/scores), data driven patterns (factor or cluster analysis), reduced rank regression, or other methods, including clinical trials; - Multi-component intervention in which the isolated effect of the dietary pattern on the outcome(s) of interest is provided or can be determined; [underlined: Excluded:]; - Studies that do not provide a description of the dietary pattern, which at minimum, must include the foods and beverages in the pattern (i.e., studies that examine a labeled dietary pattern, but do not describe the foods and beverages consumed in each intervention/exposure and comparator group); - Multi-component intervention in which the isolated effect of the dietary pattern on the outcome(s) of interest is not analyzed or cannot be determined (e.g., due to multiple intervention components within groups | - No change other than formatting to clarify intent of the criteria.
Comparator | [underlined: Included:]; - Adherence to a different dietary pattern; - Different levels of adherence to a dietary pattern; [underlined: Excluded:]; - N/A | [underlined: Included:]; - Consumption of and/or adherence to a different dietary pattern; - Different levels of consumption of and/or adherence to a dietary pattern; [underlined: Excluded:]; - Consumption of and/or adherence to a similar dietary pattern of which only a specific component or food source s differs between groups | - No change other than formatting
Outcome(s) | [underlined: Included:]; - Glucose tolerance; - Insulin resistance; - Incidence of Type 2 Diabetes; [underlined: Excluded:]; - Urinary measures of glucose | [underlined: Included:]; All included study designs in children (birth to 19 years) and interventions only in adults (19 years and older):; - Fasting blood glucose; - Fasting insulin; - Glucose tolerance/insulin resistance; - Hemoglobin A1C; - Prediabetes; All included study designs in all included age groups:; - Type 2 diabetes; [underlined: Excluded:]; - Gestational diabetes mellitus; - Urinary measures of glucose; - Non-fasting blood glucose or insulin | - Outcome criteria were modified to enable focus on the strongest body of evidence
Confounders | [underlined: Included]; - n/a; [underlined: Excluded]; - n/a | [underlined: Included]; - Studies that control for at least one of the key confounders listed in the analytic framework; [underlined: Excluded]; - Studies that control for at least one of the key confounders listed in the analytic framework | - Criteria were added to enable focus on a stronger body of evidence
Study duration | [underlined: Included]; - n/a; [underlined: Excluded]; - n/a | [underlined: Included]; - Intervention length ≥12 weeks; [underlined: Excluded]; - Intervention length <12 weeks | - Study duration criteria were modified to enable focus on the strongest body of evidence
Size of study groups | [underlined: Included]; - Randomized or nonrandomized controlled trial with at least 30 subjects per study arm and a follow-up rate of at least 80 percent, or a prospective cohort study; [underlined: Excluded]; - Studies with less than 30 subjects per study arm or a follow-up rate of less than 80 percent | [underlined: Included]; - For intervention studies:; - ≥30 participants per study group for between-subject analyses,; - or a power calculation indicating that the study is appropriately powered for the outcome(s) of interest; - For observational studies:; - Analytic sample size of ≥1000 participants (only for adults and older adults); [underlined: Excluded]; - For intervention studies:; - <30 participants per study group for between-subject analyses,; - and no power calculation indicating that the study is appropriately powered for the outcome(s) of interest; - For observational studies:; - An analytic sample size of <1,000 participants (only for adults and older adults) | - Size of study groups criteria were modified to enable focus on the strongest body of evidence
Publication status | [underlined: Included]; - Peer-reviewed articles published in research journals; [underlined: Excluded]; - Non-peer reviewed articles, unpublished data or manuscripts, pre-prints, reports, and conference abstracts or proceedings | [underlined: Included]; - Peer-reviewed articles published in research journals; [underlined: Excluded]; - Non-peer reviewed articles, unpublished data or manuscripts, pre-prints, reports, and conference abstracts or proceedings | - No change
Language | [underlined: Included]; - Published in English; [underlined: Excluded]; - Not published in English | [underlined: Included]; - Published in English; [underlined: Excluded]; - Not published in English | - No change
Country^*^; * The classification of countries on the Human Development Index (HDI) is based on the UN Development Program Human Development Report Office (http://hdr.undp.org/en/data) for the year the study intervention occurred, or data were collected. If the study does not report the year(s) in which the intervention/exposure data were collected, the HDI classification for the year of publication is applied. Studies conducted prior to 1990 are classified based on 1990 HDI classifications. If the year is more recent than the available HDI values, then the most recent HDI classifications are used. If a country is not listed in the HDI, then the current country classification from the World Bank is used (The World Bank. World Bank country and lending groups. Available from: https://datahelpdesk.worldbank.org/knowledgebase/articles/906519-world-country-and-lending-groups) | [underlined: Included]; - Subject populations from countries with high or very high human development, according to the 2011 Human Development Index; [underlined: Excluded]; - Studies conducted in countries classified as medium or low on the 2011 Human Development Index. | [underlined: Included]; - Studies conducted in countries classified as high or very high on the Human Development Index the year(s) the intervention/exposure data were collected; [underlined: Excluded]; - Studies conducted in countries classified as medium or low on the Human Development Index the year(s) the intervention/exposure data were collected | - NESR now applies the Human Development Index classification from the year in which the intervention or exposure data were collected.