# Appendix 2 Conclusion statements from the existing systematic reviews

Table A 2 Conclusion statements from the existing systematic review(s) for the research question: What is the relationship between dietary patterns consumed and risk of type 2 diabetes?

Citation | Conclusion statement and grade
Dietary Patterns Technical Expert Collaborative and NESR Staff. A Series of Systematic Reviews on the Relationship Between Dietary Patterns and Health Outcomes. March 2014. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://nesr.usda.gov/sites/default/files/2019-06/DietaryPatternsReport-FullFinal2.pdf | There is limited evidence that adherence to a dietary pattern rich in fruits, vegetables, legumes, cereals/whole grains, nuts, fish, and unsaturated oils and low in meat and high-fat dairy, assessed using an index or score, is associated with decreased risk of type 2 diabetes.(Grade: III - Limited) (Index Analysis); Limited and inconsistent evidence from epidemiological studies indicates that in adults, dietary patterns derived using factor or cluster analysis, characterized by vegetables, fruits, and low-fat dairy products tend to have an association with decreased risk of type 2 diabetes and those patterns characterized by red meat and sugar-sweetened foods and drinks, French fries, refined grains, and high-fat dairy products tended to show an increased association for risk of type 2 diabetes. Among studies, there was substantial variation in food group components and not all studies with similar patterns showed significant association.(Grade: III - Limited) (Factor or Cluster Analysis); There is insufficient evidence on a relationship between adherence to a Mediterranean-style or vegetarian diet pattern and incidence of type 2 diabetes. There is limited, inconsistent evidence that adherence to a Mediterranean-style, DASH or modified DASH, or Nordic dietary pattern results in improved glucose tolerance and insulin resistance.(Grade: IV - Not Assignable - Incidence of type 2 diabetes; Grade: III - Limited - Glucose tolerance and insulin resistance) (Other Methods); There is insufficient evidence, due to a small number of studies, to examine the relationship between dietary patterns derived using reduced rank regression and risk of type 2 diabetes. The differences in the methods used and populations studied made it difficult to compare results, and therefore no conclusions were drawn.(Grade: IV - Not Assignable) (Reduced Rank Regression)
Boushey C, Ard J, Bazzano L, Heymsfield S, Mayer-Davis E, Sabaté J, Snetselaar L, Van Horn L, Schneeman B, English LK, Bates M, Callahan E, Butera G, Terry N, Obbagy J. Dietary Patterns and Growth, Size, Body Composition, and/or Risk of Overweight or Obesity: A Systematic Review. July 2020. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.DGAC2020.SR0101 | The 2020 Dietary Guidelines Advisory Committee reviewed newly published evidence using a systematic evidence scan and determined that the conclusion drawn by the 2015 Dietary Guidelines Advisory Committee generally reflects the current state of science: Moderate evidence indicates that healthy dietary patterns higher in vegetables, fruits, and whole grains and lower in red and processed meats, high-fat dairy products, refined grains, and sweets/sugar-sweetened beverages reduce the risk of developing type 2 diabetes. 2015 Dietary Guidelines Advisory Committee Grade: Moderate; Insufficient evidence is available to determine the relationship between dietary patterns consumed by children or adolescents and risk of type 2 diabetes. Grade: Grade Not Assignable