# References of included articles in the systematic review

1 Abraham EC, Godwin J, Sherriff A, Armstrong J. Infant feeding in relation to eating patterns in the second year of life and weight status in the fourth year. Public Health Nutr. Sep 2012;15(9):1705–14. doi:10.1017/S1368980012002686 22626031
2 Agnihotri N, Overby NC, Bere E, Wills AK, Brantsaeter AL, Hillesund ER. Childhood adherence to a potentially healthy and sustainable Nordic diet and later overweight: The Norwegian Mother, Father and Child Cohort Study (MoBa). Matern Child Nutr. Apr 2021;17(2):e13101. doi:10.1111/mcn.13101 33103349
3 Baird J, Poole J, Robinson S, . Milk feeding and dietary patterns predict weight and fat gains in infancy. Paediatr Perinat Epidemiol. Nov 2008;22(6):575–86.19000296
4 Robinson SM, Marriott LD, Crozier SR, . Variations in infant feeding practice are associated with body composition in childhood: a prospective cohort study. J Clin Endocrinol Metab. Aug 2009;94(8):2799–805. doi:10.1210/jc.2009-0030 19435826
5 Vadiveloo M, Tovar A, Ostbye T, Benjamin-Neelon SE. Associations between timing and quality of solid food introduction with infant weight-for-length-scores at 12 months: Findings from the Nurture cohort. Article. Appetite. Oct 1 2019;141doi:ARTN 10429910.1016/j.appet.2019.05.030
6 Arruda Neta AC, Farias Junior JC, Lima Ferreira FE, Marchioni DM. Prospective association between dietary patterns and BMI Z-score in Brazilian adolescents. Public Health Nutr. Sep 2021;24(13):4230–4237. doi:10.1017/S1368980021000252 33472719
7 Bawaked RA, Fernandez-Barres S, Navarrete-Munoz EM, . Impact of lifestyle behaviors in early childhood on obesity and cardiometabolic risk in children: Results from the Spanish INMA birth cohort study. Pediatr Obes. Mar 2020;15(3):e12590. doi:10.1111/ijpo.12590 31793235
8 Biazzi Leal D, Altenburg de Assis MA, Hinnig PF, . Changes in Dietary Patterns from Childhood to Adolescence and Associated Body Adiposity Status. Nutrients. Oct 6 2017;9(10)doi:10.3390/nu9101098
9 Chang K, Khandpur N, Neri D, . Association Between Childhood Consumption of Ultraprocessed Food and Adiposity Trajectories in the Avon Longitudinal Study of Parents and Children Birth Cohort. JAMA Pediatr. Sep 1 2021;175(9):e211573. doi:10.1001/jamapediatrics.2021.1573 34125152
10 Costa CS, Rauber F, Leffa PS, Sangalli CN, Campagnolo PDB, Vitolo MR. Ultra-processed food consumption and its effects on anthropometric and glucose profile: A longitudinal study during childhood. Nutr Metab Cardiovasc Dis. Feb 2019;29(2):177–184. doi:10.1016/j.numecd.2018.11.003 30660687
11 Costa CDS, Assuncao MCF, Loret de Mola C, . Role of ultra-processed food in fat mass index between 6 and 11 years of age: a cohort study. Int J Epidemiol. Mar 3 2021;50(1):256–265. doi:10.1093/ije/dyaa141 32888008
12 Costa CDS, Buffarini R, Flores TR, Neri D, Freitas Silveira M, Monteiro CA. Consumption of ultra-processed foods and growth outcomes in early childhood: 2015 Pelotas Birth Cohort. Br J Nutr. Sep 12 2022:1–8. doi:10.1017/S0007114522002926
13 Cunha DB, da Costa THM, da Veiga GV, Pereira RA, Sichieri R. Ultra-processed food consumption and adiposity trajectories in a Brazilian cohort of adolescents: ELANA study. Nutr Diabetes. May 25 2018;8(1):28. doi:10.1038/s41387-018-0043-z 29795367
14 Durao C, Severo M, Oliveira A, . Association between dietary patterns and adiposity from 4 to 7 years of age. Public Health Nutrition. Aug 2017;20(11):1973–1982. doi:10.1017/S1368980017000854 28534458
15 Durao C, Severo M, Oliveira A, Lopes C. Sex-Heterogeneity on the Association between Dietary Patterns at 4 Years of Age with Adiposity and Cardiometabolic Risk Factors at 10 Years of Age. Article. Nutrients. Jan 26 2022;14(3)doi:10.3390/nu14030540
16 Gasser CE, Mensah FK, Clifford SA, Kerr JA, Cassim R, Wake M. Bidirectional associations between diet and body composition measures from 2 to 15 years: Longitudinal Study of Australian Children. Article. British Journal of Nutrition. Jan 28 2019;121(2):212–220. doi:10.1017/S0007114518003173 30375296
17 Pereyra Gonzalez I, Farias-Antunez S, Buffarini R, . Ultra-processed food consumption and the incidence of obesity in two cohorts of Latin-American young children: A longitudinal study. J Pediatr Nurs. Mar–Apr 2023;69:e120–e126. doi:10.1016/j.pedn.2022.12.018 36604255
18 Heerman WJ, Sneed NM, Sommer EC, . Ultra-processed food consumption and BMI-Z among children at risk for obesity from low-income households. Pediatr Obes. Aug 2023;18(8):e13037. doi:10.1111/ijpo.13037 37070567
19 Hennessy A, McCarthy EK, Ni Chaoimh C, Murray DM, Kiely ME. Poor Quality Diets Characterized by Low-Nutrient Density Foods Observed in One-Quarter of 2-Year-Olds in a High Resource Setting. Article in Press. J Nutr. Sep 2023;153(9):2678–2688. doi:10.1016/j.tjnut.2023.06.029 37356499
20 Marinho AR, Severo M, Vilela S, . Is the association between dietary patterns and cognition mediated by children’s adiposity? A longitudinal approach in Generation XXI birth cohort. Clin Nutr. Jan 2022;41(1):231–237. doi:10.1016/j.clnu.2021.11.029 34915274
21 Marks J, Barnett LM, Allender S. Change of School in Early Adolescence and Adverse Obesity-Related Dietary Behavior: A Longitudinal Cohort Study, Victoria, Australia, 2013-2014. Prev Chronic Dis. Sep 10 2015;12:E145. doi:10.5888/pcd12.150042 26355826
22 Oellingrath IM, Svendsen MV. BMI-specific associations between health-related behaviours and overweight - a longitudinal study among Norwegian adolescents. Public Health Nutr. Feb 2017;20(3):481–491. doi:10.1017/S1368980016002536 27652897
23 Pala V, Lissner L, Hebestreit A, . Dietary patterns and longitudinal change in body mass in European children: a follow-up study on the IDEFICS multicenter cohort. Article. Eur J Clin Nutr. Oct 2013;67(10):1042–9. doi:10.1038/ejcn.2013.145 23942180
24 Saldanha-Gomes C, Heude B, Charles MA, . Prospective associations between energy balance-related behaviors at 2 years of age and subsequent adiposity: the EDEN mother-child cohort. Int J Obes (Lond). Jan 2017;41(1):38–45. doi:10.1038/ijo.2016.138 27528250
25 Saldanha-Gomes C, Hallimat Cisse A, Descarpentrie A, . Prospective associations between dietary patterns, screen and outdoor play times at 2 years and age at adiposity rebound: The EDEN mother-child cohort. Article. Prev Med Rep. Feb 2022;25:101666. doi:10.1016/j.pmedr.2021.101666 35127350
26 Sirkka O, Fleischmann M, Abrahamse-Berkeveld M, . Dietary Patterns in Early Childhood and the Risk of Childhood Overweight: The GECKO Drenthe Birth Cohort. Article. Nutrients. Jun 15 2021;13(6)doi:10.3390/nu13062046
27 Smith ADAC, Emmett PM, Newby PK, Northstone K. Dietary patterns and changes in body composition in children between 9 and 11 years. Food & Nutrition Research. 2014;58doi:ARTN 22769 10.3402/fnr.v58.22769
28 Vedovato GM, Vilela S, Severo M, Rodrigues S, Lopes C, Oliveira A. Ultra-processed food consumption, appetitive traits and BMI in children: a prospective study. Br J Nutr. Jun 28 2021;125(12):1427–1436. doi:10.1017/S0007114520003712 32962770
29 Vilela S, Magalhaes V, Severo M, Oliveira A, Torres D, Lopes C. Effect of the food processing degree on cardiometabolic health outcomes: A prospective approach in childhood. Clin Nutr. Oct 2022;41(10):2235–2243. doi:10.1016/j.clnu.2022.07.034 36081298
30 Wolters M, Joslowski G, Plachta-Danielzik S, . Dietary Patterns in Primary School are of Prospective Relevance for the Development of Body Composition in Two German Pediatric Populations. Nutrients. Oct 5 2018;10(10)doi:10.3390/nu10101442
31 Beslay M, Srour B, Mejean C, . Ultra-processed food intake in association with BMI change and risk of overweight and obesity: A prospective analysis of the French NutriNet-Sante cohort. PLoS Med. Aug 2020;17(8):e1003256. doi:10.1371/journal.pmed.1003256 32853224
32 Calvo-Malvar M, Benitez-Estevez AJ, Leis R, Sanchez-Castro J, Gude F. Changes in Dietary Patterns through a Nutritional Intervention with a Traditional Atlantic Diet: The Galiat Randomized Controlled Trial. Article. Nutrients. Nov 25 2021;13(12)doi:10.3390/nu13124233
33 Canhada SL, Luft VC, Giatti L, . Ultra-processed foods, incident overweight and obesity, and longitudinal changes in weight and waist circumference: the Brazilian Longitudinal Study of Adult Health (ELSA-Brasil). Public Health Nutr. Apr 2020;23(6):1076–1086. doi:10.1017/S1368980019002854 31619309
34 Canhada SL, Vigo A, Luft VC, . Ultra-Processed Food Consumption and Increased Risk of Metabolic Syndrome in Adults: The ELSA-Brasil. Diabetes Care. Feb 1 2023;46(2):369–376. doi:10.2337/dc22-1505 36516280
35 Cordova R, Kliemann N, Huybrechts I, . Consumption of ultra-processed foods associated with weight gain and obesity in adults: A multi-national cohort study. Clin Nutr. Sep 2021;40(9):5079–5088. doi:10.1016/j.clnu.2021.08.009 34455267
36 Gonzalez-Palacios S, Oncina-Canovas A, Garcia-de-la-Hera M, . Increased ultra-processed food consumption is associated with worsening of cardiometabolic risk factors in adults with metabolic syndrome: Longitudinal analysis from a randomized trial. Atherosclerosis. Jul 2023;377:12–23. doi:10.1016/j.atherosclerosis.2023.05.022 37343432
37 Konieczna J, Morey M, Abete I, . Contribution of ultra-processed foods in visceral fat deposition and other adiposity indicators: Prospective analysis nested in the PREDIMED-Plus trial. Clin Nutr. Jun 2021;40(6):4290–4300. doi:10.1016/j.clnu.2021.01.019 33610419
38 Li M, Shi ZM. Ultra-Processed Food Consumption Associated with Overweight/Obesity among Chinese Adults-Results from China Health and Nutrition Survey 1997-2011. Nutrients. Aug 2021;13(8):2796. doi:ARTN 2796 10.3390/nu13082796 34444957
39 Livingstone KM, Brayner B, Celis-Morales C, Ward J, Mathers JC, Bowe SJ. Dietary patterns, genetic risk, and incidence of obesity: Application of reduced rank regression in 11,735 adults from the UK Biobank study. Prev Med. May 2022;158:107035. doi:10.1016/j.ypmed.2022.107035 35346749
40 Mendonca RD, Pimenta AM, Gea A, . Ultraprocessed food consumption and risk of overweight and obesity: the University of Navarra Follow-Up (SUN) cohort study. Am J Clin Nutr. Nov 2016;104(5):1433–1440. doi:10.3945/ajcn.116.135004 27733404
41 Mirmiran P, Moslehi N, Golzarand M, Azizi F. Ultra-processed foods consumption and the risk of metabolically unhealthy phenotype in normal-weight and overweight/obese adults: a prospective investigation. Int J Food Sci Nutr. 2023;74(4):522–531. doi:10.1080/09637486.2023.2222935 37334484
42 Pant A, Gribbin S, Machado P, . Ultra-processed foods and incident cardiovascular disease and hypertension in middle-aged women. Eur J Nutr. Apr 2024;63(3):713–725. doi:10.1007/s00394-023-03297-4 38147150
43 Rauber F, Chang K, Vamos EP, . Ultra-processed food consumption and risk of obesity: a prospective cohort study of UK Biobank. Eur J Nutr. Jun 2021;60(4):2169–2180. doi:10.1007/s00394-020-02367-1 33070213
44 Rudakoff LCS, Magalhaes E, Viola P, . Ultra-processed food consumption is associated with increase in fat mass and decrease in lean mass in Brazilian women: A cohort study. Front Nutr. 2022;9:1006018. doi:10.3389/fnut.2022.1006018 36313106
45 Santos FSD, Martinez Steele E, Costa CDS, . Nova diet quality scores and risk of weight gain in the NutriNet-Brasil cohort study. Article in Press. Public Health Nutr. Nov 2023;26(11):2366–2373. doi:10.1017/S1368980023001532 37522809
46 Tan LJ, Hwang SB, Shin S. The Longitudinal Effect of Ultra-Processed Food on the Development of Dyslipidemia/Obesity as Assessed by the NOVA System and Food Compass Score. Mol Nutr Food Res. Oct 2023;67(20):e2300003. doi:10.1002/mnfr.202300003 37650269
47 Cummings JR, Lipsky LM, Schwedhelm C, Liu A, Nansel TR. Associations of ultra-processed food intake with maternal weight change and cardiometabolic health and infant growth. Int J Behav Nutr Phys Act. May 26 2022;19(1):61. doi:10.1186/s12966-022-01298-w 35619114
48 Dias LM, Schmidt MI, Vigo A, Drehmer M. Dietary Patterns in Pregnancy and the Postpartum Period and the Relationship with Maternal Weight up to One Year after Pregnancy Complicated by Gestational Diabetes. Nutrients. Oct 5 2023;15(19)doi:10.3390/nu15194258