# Summary of conclusion statements and grades

The 2025 Dietary Guidelines Advisory Committee answered the systematic review question, “What is the relationship between consumption of dietary patterns with varying amounts of ultra-processed foods and growth, body composition, and risk of obesity?”, with the following conclusion statement[s].^*^ The grades reflect the strength of the evidence underlying the conclusion statements.

* A conclusion statement is carefully constructed, based on the evidence reviewed, to answer the systematic review question. A conclusion statement does not draw implications and should not be interpreted as dietary guidance.

### Infants and Young Children up to age 24 months

- A conclusion statement cannot be drawn about the relationship between dietary patterns consumed by infants and young children up to age 24 months with varying amounts of ultra-processed food and growth, body composition, and risk of obesity because of substantial concerns with consistency and directness in the body of evidence. (Grade Not Assignable)

### Children and Adolescents

- Dietary patterns consumed by children and adolescents with higher amounts of foods classified as ultra-processed food are associated with greater adiposity (fat mass, waist circumference, BMI) and risk of overweight. This conclusion statement is based on evidence grade as limited. (Grade: Limited)

### Adults and Older Adults

- Dietary patterns consumed by adults and older adults with higher amounts of foods classified as ultra-processed food are associated with greater adiposity (fat mass, waist circumference, BMI) and risk of obesity and/or overweight. This conclusion statement is based on evidence grade as limited. (Grade: Limited)

### Pregnancy and Postpartum

- A conclusion statement cannot be drawn about the relationship between dietary consumed during pregnancy patterns with varying amounts of ultra-processed food and gestational weight gain because there is not enough evidence available. (Grade Not Assignable)
- A conclusion statement cannot drawn about the relationship between dietary patterns consumed during postpartum with varying amounts of ultra-processed food and body composition, and risk of obesity because there is not enough evidence available. (Grade Not Assignable)

## Research recommendations

- Conduct well-controlled trials in the U.S. that examine dietary patterns with higher compared to lower amounts of ultra-processed food (UPF) that are matched for energy-density and conducted over an intervention length ≥ 12 weeks in relation to growth, body composition, and risk of obesity outcomes. Not controlling for diet quality limits the ability to isolate the effects on outcomes due to the differences in UPF from differences in diet quality. Trials that last less than 12 weeks provide limited information on the long-term health impacts on growth, body composition, and risk of obesity outcomes from dietary pattern consumption.
- Replicate findings from observational studies conducted outside of the U.S with prospective cohort studies among populations in the U.S while considering diversity in race and/or ethnicity, socioeconomic position, gender identity, and health disparities. Studies conducted outside of the U.S. in homogenous populations limit generalizability due to differences in food supply and lack of participant diversity.
- Examine dietary patterns with varying amounts of UPF consumed and growth, body composition, and risk of overweight/obesity, across life stages with particular evidence gaps. Limited studies are available that administer dietary assessments in infants and young children up to age 24 months, adolescents, older adults, and individuals during pregnancy and postpartum.
- Conduct repeat measures of dietary patterns and health outcomes for analyses of longitudinal associations between diet and change in outcomes over time. Studies examining dietary patterns based on a single diet assessment (often at baseline only) and outcome measure do not capture changes in dietary intake and outcomes over time.
- Enhance food surveillance capacity that provides access to the types and amounts of processing ingredients (e.g., emulsifiers, additives, colorants) in food composition databases. Available databases do not provide this information, which limits the ability to understand how and when foods consumed in dietary patterns shift from “processed” to “ultraprocessed.”
- Design diet assessment tools specifically to assess varying amounts of UPF within different dietary patterns that are validated for the population of interest (e.g., postpartum). Studies that use dietary intake assessments that were not designed to assess UPF specifically pose higher risk of bias due to potential exposure misclassification.
- Examine dietary patterns with varying amounts of UPF, based on a variety of classification systems (e.g., SIGA), in relation to health outcomes. Studies that use only one classification system (Nova) or no specific classification or definition for UPF limit robustness of the available evidence.
- Quantify the amounts of individual UPF within dietary patterns consumed by participants as total weight (e.g., g/d) and contribution to overall dietary intake (e.g., % energy). Studies that do not provide this context make it difficult to compare UPF intake across studies and define low vs. high amounts of UPF.
- Collect outcome measures of growth, body composition, and obesity in-person, using standardized procedures. Studies that rely on self-report of outcome measures and do not apply standard cut-offs to capture growth, body composition, and risk of obesity pose higher risk of bias due to outcome measurement error and may limit the comparability across findings.
- Assess weight change earlier in pregnancy or preferably pre-pregnancy, rather than from mid- or late-pregnancy. Studies that only examine weight change from mid to late pregnancy may be more prone to error in outcome measurement due to the limited duration of pregnancy.
- Control for key confounding factors, which include: race and/or ethnicity, socioeconomic position, social determinants of health, age, physical activity, anthropometry at baseline, and human milk and infant formula intakes among those under age 2 years. Consider stratifying analyses by those factors and/or other social determinants of health. Studies that do not analyze or adjust for these factors limit the ability to interpret the relationship between dietary patterns consumed and growth, body composition, and risk of obesity.
- Conduct sensitivity analyses by removing individual UPF components within the dietary pattern, particularly those with greater nutrient-density from naturally occurring nutrients, to better determine differences in results. Studies that do not conduct these analyses provide limited information about underlying drivers of the relationship between dietary patterns consumed and growth, body composition, and risk of obesity.
- Report descriptive information on the status of foods/food group items as homemade or commercial/industrialized and rationale for why items may meet classification as “ultra-processed, including the types and amounts of processing “formulations” or specific combinations of ingredients and additives such as emulsifiers and colorants. Studies that do not provide these details limit the ability to determine generalizability across findings.
- Report descriptive information on participant characteristics (e.g., race, ethnicity, health status). Studies that do not provide these details limit the ability to determine generalizability across findings.