# Results

## Literature search and screening results

The articles included in this systematic review were identified from two literature searches (Appendix 2). The primary literature search was conducted to identify articles examining dietary patterns with UPF and growth, body composition, and risk of obesity. That literature search yielded 3920 search results after the removal of duplicates (see Figure 2). Dual-screening resulted in the exclusion of 3335 titles, 363 abstracts, and 191 full-texts articles from that search. The results of a second literature search that was conducted for another systematic review^†^ on dietary patterns and growth, body composition, and risk of obesity was manually searched. NESR analysts identified 17 articles from that literature search that examined dietary patterns with varying amounts of UPF. Reasons for full-text exclusion are in Appendix 3. The body of evidence included 48 articles in infants and young children up to age 24 months, n=5^1–5^; children and adolescents, n=25^6–30^; adults and older adults, n=16^31–46^; and individuals during pregnancy and/or postpartum, n=2^47,48^

† Hoelscher DM, Anderson, Booth, . Dietary Patterns and Growth, Body Composition, and Risk of Obesity: A Systematic Review. Date TBD. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://nesr.usda.gov/

Figure 2 Literature search and screening flow chart

Image of flowchart of literature search and screening described fully in the text.

## Infants and young children up to age 24 months

Five articles met inclusion criteria that examined the relationship between dietary patterns with varying amounts of UPF consumed by infants and young children up to age 24 months and growth, body composition, and risk of obesity (also see Table 2). All 5 articles reported data from prospective cohort study designs.^1–5^

### Description of the evidence

#### Population

Sample size of studies ranged from 449 to 14,989 participants, conducted in 4 countries (United Kingdom (n=2), Norway (n=1), Scotland (n=1), and United States (n=1)). Two articles from the Southampton Women’s Survey cohort were included but examined dietary patterns (exposure) and outcomes at different ages. Other cohorts represented in the included articles were: Norwegian Mother, Father and Child Cohort Study; Nurture Observational Study; and Growing Up in Scotland (GUS) Study.

Studies examined dietary patterns consumed at ages ranging from 4 months up to 2 years, with most examining 6 to 12 months. Three of the articles reported some information on the racial or ethnic background of participants as follows: 1) 4% non-white; 2) 65.2% non-Hispanic Black; 3) 94% White. One study, conducted in the United States, enrolled majority (~59%) low-income participants. Socioeconomic position (SEP) was reported in 4 of the 5 articles, with maternal education being the most used proxy.

#### Intervention/exposure and comparator

All studies used food-frequency questionnaires to assess habitual consumption of individual foods and/or food groups, administered by researchers or self-administered by caregivers. All but one study collected diet at more than one time point, which had a single assessment at age 19-24 months. Approaches used to examine dietary patterns were factor/cluster analyses (n=3) or index/score analyses (n=2).

#### Outcomes

Weight, height, and/or body composition of participants was measured in-person using standard protocols, instruments and trained staff in all but one article, which collected information via parent-report.^2^ Cut points and measures used to categorize or classify participants’ outcome status were: BMI percentile, BMI z-score, or other ratios of weight-to-height (e.g., BMI reference curves vs. WHO vs. Cole’s method (https://www.scopus.com/record/display.uri?eid=2-s2.0-0034611996&origin=inward)^*^). The following outcomes were reported across the body of evidence:

- BMI, BMI z-score, or weight-for-length z-score^1,4,5^
- Adiposity (e.g. fat mass),^3,4^
- Risk of overweight and/or obesity,^1,2^
- Weight/weight gain,^1–5^
- Length/length gain^3^

* Cole, T.J., Bellizzi, M.C., Flegal, K.M., Dietz, W.H. Establishing a standard definition for child overweight and obesity worldwide: International survey. British Medical Journal 2000;320(7244):1240–1243.10797032

### Synthesis of the evidence

None of the studies and/or dietary patterns were designed specifically to examine varying amounts of UPF within dietary patterns and their association with the outcomes of interest. The mean intakes of UPF in the study populations were not reported.

Across all studies, the results varied for both the direction and magnitude of effect estimates from analyses comparing participants consuming dietary patterns that reflected higher compared to lower amounts of foods that are typically classified as UPF.^1–5^ Two articles reported no associations between dietary patterns varying in UPF and risk of overweight or obesity.^1,2^ Three studies reported no association with dietary patterns varying in UPF and BMI z-score, weight-for-length z-score, and/or BMI.^1,2,3,4^ One study observed that a dietary pattern with fewer UPF was associated with lower weight-for-length z-score, but other dietary patterns were not associated with weight-for-length z-score when compared to the dietary pattern with the most UPF.^5^ One study observed a positive association between dietary patterns higher in UPF and weight gain between 6-12 months of age, but not weight through follow-up at age 12 months.^3^

### Conclusion statement and grade

The 2025 Dietary Guidelines Advisory Committee did not develop a conclusion statement to answer the question because of substantial concerns with consistency and directness in the available evidence (Table 5). Studies also had numerous concerns due to risk of bias (Table 7). This body of evidence includes both large and small studies, including studies with smaller sample sizes and null findings, which makes publication bias less likely.

Table 5 Conclusion statement, grades for dietary patterns with varying amounts of ultra-processed food consumed by infants and young children, up to age 24 months, and growth, body composition, and risk of obesity

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between dietary patterns consumed by infants and young children up to age 24 months with varying amounts of ultra-processed food and growth, body composition, and risk of obesity because of substantial concerns with consistency and directness in the body of evidence.
Grade | Grade not assignable
Body of Evidence | 5 articles from prospective cohort studies
Rationale | Critical limitations in the consistency across the body of evidence for the timing of exposure and outcome assessments, reporting of outcomes, and direction and magnitude of effect estimates. Dietary assessment methods and the derived dietary patterns were not designed to quantify UPF intake, which substantially limited the ability to adequately assess the evidence, particularly for directness.

Table 6 Studies examining the relationship between dietary patterns with varying amounts of ultra-processed food consumed by infants and young children up to age 24 months and growth, body composition and composition and risk of obesity^a^

Article Information | Intervention/exposure and comparator | Results | Methodological considerations
Abraham, 2012 ^1^; Scotland; Growing Up in Scotland (GUS) study (20052008); Analytic N=4493; Participant characteristics: NR; 4% non-white ethnic group (Bradshaw, 2007); NR; Variables with >5% missing responses excluded from cluster analysis. Excluded infants with missing data points for models in Tables 2 and 3. | Age at Dietary Pattern: 19 to 24 months; [underlined: Cluster 1 (Negative)]: low fruit, vegetable; high sweets, crisps, soft drinks, snacking; [underlined: Cluster 2 (Positive):] high fruit, vegetable; low snacking; Method(s): Factor/Cluster | Age at Follow-up: 4 years; Frequency of Overweight/Obesity at 45-48 months: 12.5% vs. 11.9%, P=0.598, NS; Cluster 1 v. Cluster 2, ref & BMI z-score: 0.96, 95% CI: 0.76, 1.21 | - Diet assessed via FFQ; - Cannot determine whether groups were similar at baseline on key characteristics; - Bradshaw, 2007 summarizes Sweep 1 baseline characteristics; Funding: Growing Up in Scotland (GUS) data set received no specific grant from any funding agency in the public, commercial or not-for profit sector.
Agnihotri, 2021 ^2^; Norway; Norwegian Mother, Father and Child Cohort Study (MoBa); Analytic N=14989; Participant characteristics:49.7% female; NR; 30% ≤ 12y maternal education; Enrolled mothers during pregnancy; Excluded if missing data from Medical Birth Registry of Norway; missing questionnaire data during pregnancy; multiple pregnancies; additional pregnancies by same mother; extreme intake during pregnancy; child age <7 or >9.5 years at outcome; missing outcome data; anthropometric data outside +/− 4 SD | Age at Dietary Pattern:6 months, 18 months; [underlined: New Nordic Diet (NND) score, 6 months]: Positive: homemade Fruit puree (v. commercial); homemade Dinners (v. commercial); homemade Porridge (v. commercial); Exclusive breast-fed ≥4 months; Any breast-fed at 6 months; Water (v. sweetened beverages); Method(s):Index or Score Analysis | Age at Follow-up: 8 years; NND at 6 months & Risk of Overweight; - Low, OR: 1.00, ref; - Medium, OR: 1.05, 95% CI: 0.93, 1.16; p-trend=0.402; - High, OR: 0.97, 95% CI: 0.83, 1.13; p-trend=0.724; - Per 1-pt, OR: 0.99, 95% CI: 0.96, 1.03; p-trend=0.773 | - Diet assessed at two times using FFQ via maternal-report, but FFQ and components varied; - Overweight assessed from BMI computed from parent-reported child height & weight at 8 years; Funding: Norwegian Ministry of Health and Care Services, Ministry of Education and Research
Baird, 2008^3^; United Kingdom; Southampton Women’s Survey (SWS); Analytic N=1740; Participant characteristics:; 46.9% female; 94% white; Maternal educational attainment:; - None, 2%;; - GCSE D-G, 10%;; - GCSE A-C, 28%;; - A levels, 30%;; - HND, 8%;; - Degree, 22%; Excluded multiples and preterm births | Age at Dietary Pattern: 6 months; [underlined: ‘Infant Guidelines’]: high frequency of consumption of vegetables, fruit, meat, fish, home-prepared foods, breast milk; low frequency of consumption of commercial baby foods in jars and formula; [underlined: ‘Adult Foods’]: high frequency of consumption of bread, savory snacks, biscuits, squash, breakfast cereals, and crisps; low frequency of breast milk, baby rice, and cooked and canned fruit; Method(s): Factor/Cluster | Age at Follow-up: 12 months; ‘Infant Guidelines’; - Skinfold thickness; ○ 6-12 months, β: 0.11, 95% CI: 0.04, 0.18; P-value: 0.002; ○ at 12 months, β: 0.13, 95% CI: 0.01, 0.25; p=0.03; - Weight; ○ 6-12 months, β: 0.10, 95%CI: 0.04, 0.17; p=0.002; ○ at 12 months, β: 0.07, 95% CI: −0.01, 0.14; p=0.09; - Length; ○ 6-12 months, β: 0.03, 95%CI: −0.04, 0.10; p=0.225; ○ at 12 months; β: 0.04, 95% CI: −0.13, 0.21; p=0.612; ‘Adult foods’; - Skinfold thickness; ○ 6-12 months: β: 0.00, 95% CI: −0.07, 0.07; p= 0.92; ○ at 12 months: β: 0.01, 95% CI: −0.12, 0.13; p=0.89; - Weight; ○ 6-12 months, β:−0.08, 95%CI: −0.15, −0.02; p=0.0015; ○ at 12 months, β: 0.02, 95% CI: −0.06, 0.10; P=0.60; - Length; ○ 6-12 months, β:−0.04, 95%CI: −0.11, 0.03; p=0.225; ○ at 12 months; β: 0.00, 95% CI: −0.17, 0.17; p=0.984 | - Diet assessed with repeat measures using FFQ via maternal-report; - Weight, length, body composition measured; - Cannot determine whether groups were similar at baseline; - Unclear whether outcome assessors were blinded to the infants’ feeding histories; - Ethnic minorities were underrepresented in this sample.; - Funding: UK Medical Research Council; University of Southampton British Heart Foundation Food Standards Agency Dunhill Medical Trust
Robinson, 2009 ^4^; United Kingdom; Southampton Women’s Survey; Analytic N=536; Participant characteristics:; 47% Female; Race/ethnicity NR; Maternal educational attainment: lower than A-levels, ~38-49%; A-levels or higher, ~62-51%; Singletons, who were followedup from birth until age 4 years. | Age at Dietary Pattern: 12 months; [underlined: ‘Infant guidelines pattern’:] High consumption of fruit, vegetables, cooked meat and fish, and other home-prepared foods (rice, pasta), and low consumption of commercial baby foods; Method(s): Factor/Cluster | Age at Follow-up: 4 years; mean lean mass (kg); - < −0.68: 12.0, 95% CI: 11.7, 12.4; - −0.68 to 0: 12.3, 95% CI: 12.1, 12.6; - 0 to 0.68: 12.7, 95% CI: 12.4, 12.9; - ≥0.68: 12.6, 95% CI: 12.3, 12.9; P-trend: 0.003; mean lean mass index (kg/m^2^); - <−0.68: 11.7, 95% CI: 11.5, 11.9; - −0.68 to 0: 11.8, 95% CI: 11.6, 11.9; - 0 to 0.68: 11.9, 95% CI: 11.8, 12.0; - ≥0.68: 11.9, 95% CI: 11.8, 12.1; P-trend: 0.004; mean fat mass (kg); - <−0.68: 4.5, 95% CI: 4.3, 4.7; - −0.68 to 0: 4.7, 95% CI: 4.5, 4.9; - 0 to 0.68: 4.7, 95% CI: 4.5, 4.9; - ≥0.68: 4.5, 95% CI: 4.3, 4.6 P-trend: 0.781; mean fat mass index (kg); - <−0.68: 4.3, 95% CI: 4.1, 4.4; - −0.68 to 0: 4.3, 95% CI: 4.2, 4.5; - 0 to 0.68: 4.3, 95% CI: 4.2, 4.5; - ≥0.68: 4.1, 95% CI: 4.0, 4.3; P-trend: 0.488; mean BMI (kg/m^2^); - <−0.68: 15.9, 95% CI: 15.6, 16.1; - −0.68 to 0: 16.1, 95% CI: 15.8, 16.3; - 0 to 0.68: 16.2, 95% CI: 16.0, 16.5; - ≥0.68: 16.1, 95% CI: 15.8, 16.3; P-trend: 0.102 | - Diet assessed with repeat measures (age 6, 12 months) using FFQ and maternal interview; - Weight/Height measured and other outcomes via DXA; - Cannot determine whether groups were similar at baseline on key characteristics; - Cannot determine whether outcome assessors were blinded; - Did not define age of introduction of complementary foods and beverages variable; - Did not account for high loss to follow-up (55%); - Funding: Medical Research Council, University of Southampton, British Heart Foundation, Food Standards Agency
Vadiveloo, 2019 ^5^; United States; Nurture Cohort; Analytic N=449; Participant characteristics:; SEP: 65.2% non-Hispanic Black; 59.3% low income (<$20K/year); 18.9% mothers <high school education; Recruited mothers between 20 and 36 weeks’ gestation; Excluded mothers <18 years; mothers without singleton pregnancy; without intention to remain in study area for at least 12 months; with missing dietary or outcome data | Age at Dietary Pattern: 4 to 12 months; [underlined: Healthy Food Score (HFS)]: Positive: Vegetables (no fried potatoes); Fruit (no 100% fruit juice); [underlined: Unhealthy Food Score (UnHFS)]: Positive: French Fries; Ice cream; Baby Snacks; Sweets; Healthiest (10 points) = ≥ 2 servings/d of foods in HFS AND ≤ 1 serving/d of foods in UnFS; [underlined: Moderately healthy] (0 points) = ≥ 2 servings/day of foods in HFS AND ≤ 1 serving/day of foods in UnHFS; [underlined: Moderately unhealthy] (−10 points)= > 2 servings/day of foods in HFS AND > 1 serving/day of foods in UnHFS; [underlined: Unhealthy (ref)] (−20 points)= < 2 servings/day of foods included in HFS and > 1 serving/day of foods included in UnHFS; Method(s): Index or Score Analysis | Age at Follow-up: 12 months; Weight-for-length z-score, mean [standard error]; - HFS: Q1, 0.56 [0.09]; Q2, 0.64 [0.10]; Q3, 0.66 [0.09]; Q4, 0.73 [0.10]; p-trend=0.65; - UnHFS: Q1, 0.42 [0.09]; Q2, 0.63 [0.09]; Q3, 0.79 [0.09]; Q4, 0.75 [0.09]; p-trend=0.02; - Moderately unhealthy v. Unhealthy: 0.06, 95% CI: −0.17, −0.29; - Moderately healthy v. Unhealthy: −0.33, 95% CI: −0.63, −0.03, p<0.05; - Healthiest v. Unhealthy: 0.02, 95% CI: −0.30, 0.33 | - Diet assessed with repeat surveys (at ages 6, 9, and 12 months) from maternal recall and based HFS and UnHFS scores on mean value from between age 4 and 12 months.; - Insufficient data on attrition reported; - Funding: National Institutes of Health, National Institutes of Diabetes and Digestive and Kidney Diseases

a Abbreviations: BMI, body mass index; FFQ, Food frequency questionnaire; HFS, healthy food score; NR, not reported; ref, reference group/category; SD, standard deviation; SEP/SES, Socioeconomic position/status; UK, United Kingdom

Table 7 Risk of bias for observational studies examining dietary patterns with varying amounts of ultra-processed food consumed by infants and young children up to age 24 months and growth, body composition and risk of obesity^a^

Article | Confounding | Exposure classification | Participant Selection | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall
Abraham, 2012 ^1^ | High | Some concerns | Some concerns | Low | Some concerns | Some concerns | Some concerns | High
Agnihotri, 2021^2^ | High | Low | Low | Low | High | Low | Low | High
Baird, 2008^3^ | High | Low | Low | Low | Some concerns | Some concerns | Some concerns | High
Robinson, 2009 ^4^ | High | Low | Low | Low | High | Low | Some concerns | High
Vadiveloo, 2019^5^ | High | Low | Low | Low | High | Some concerns | Some concerns | High

a Possible ratings of low, some concerns, high, very high, or no information determined using the “Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)” tool ( ROBINS-E Development Group (Higgins J, Morgan R, Rooney A, . Risk Of Bias In Non-randomized Studies - of Exposure (ROBINS-E). Launch version, 1 June 2022. Available from: https://www.riskofbias.info/welcome/robins-e-tool )

## Children and adolescents

Twenty-five articles met inclusion criteria and examined the relationship between dietary patterns with varying amounts of UPF consumed by children and adolescents and growth, body composition, and risk of obesity (also see Table 4). All articles analyzed prospective cohort studies.^6–30^

### Description of the evidence

#### Population

Studies examined dietary patterns varying in UPF consumed by participants ranging in age between 2 up to 19 years. Race and/or ethnic background of participants was reported as mostly or predominantly non-White and/or Hispanic in 3 articles and predominantly White and/or non-Hispanic in 5 articles. Information on socioeconomic position (SEP) of participants widely varied across studies.

Data from 18 different countries were represented across included articles (Australia; Belgium; Brazil; Cyprus; Estonia; France; Germany; Hungary; Ireland; Italy; Netherlands; Norway; Portugal; Spain; Sweden; United Kingdom; United States; Uruguay). Multiple articles from a single cohort study were included from the following studies: Avon Longitudinal Study of Parents and Children (ALSPAC),^9,27^ the EDEN study^24,25^, Generation XXI^14,15,20,28,29^; Identification and prevention of Dietary- and lifestyle-induced health EFfects In Children and infantS (IDEFICS) and/or the Kiel Obesity Prevention Study (KOPS)^23,30^ and the Pelotas Birth Cohort study.^11,12,17^ Across these cohort studies, the different articles examined dietary patterns varying in UPF differently, such as per 100 grams or per 100 kcal increase, by different outcomes or ages, and/or by different exposure classifications for dietary patterns varying in UPF (e.g., derived scores by Nova classification groups).

#### Intervention/exposure and comparator

Dietary intake assessment methods included food frequency questionnaire (n=13), 24-hour recalls (n=5), and/or diet history/diaries or other methods (n=7). Dietary patterns varying in UPF were examined by deriving a priori score-based indices (e.g., alignment or adherence based on a pre-determined index/score),^7,9–13,17,18,21,28,29^ and data-driven methods of pattern development such as factor/cluster analysis^6,8,16,19,22–27,30^ or latent class analysis^15,20^ Ten articles examined dietary patterns with different amounts of UPF, where UPF were defined by the Nova system. Exposure to UPF within a dietary pattern was based on contribution to total energy or weight and examined continuously (such as per 100 grams amount consumed) and/or categorically (such as by tertiles or quartiles).^7,9–13,17,18,28,29^ Four articles examined consumption of a dietary pattern with UPF compared to different dietary pattern without or low in UPF.^14,15,19,20^

All included studies described the types of UPF contributing to the dietary pattern. However, the groupings of foods that were classified as UPF widely varied across studies. Common sources or types of UPF contributing to the dietary patterns included:

- sugar-sweetened beverages
- processed meats and meat products
- sugar-sweetened foods
- packaged salty/savory and/or sweet snack foods
- ready-to-eat meals and dishes

#### Outcomes

All of the included studies reported using standardized procedures to measure (in-person) body size and/or composition of participants. The following outcomes were reported in the included studies:

- Risk of overweight and/or obesity^19^
- BMI, BMI z-score, weight-to-height ratio, and/or weight-for-length z-score^6–10,12–16,18,19,23,24,28–30^
- Body composition (such as z-scores for fat mass, fat mass index, fat free mass, skinfold thickness)^10–15,24,25,27,29,30^
- Waist circumference (and waist circumference z-score or waist-hip-ratio)^7,10,12,14,15,20,29,30^
- Weight and/or height/length^9,12,19^

### Synthesis of the evidence

This evidence synthesis focuses on the studies with fewer limitations, which included studies that: (1) were designed to directly examine dietary patterns that vary in UPF; (2) used 24-hour recall or dietary records to collect dietary intake of UPF; and (3) used a food processing classification system to categorize items as UPF; Across evidence, the direction of reported effect estimates were similar, regardless of statistical significance, and suggested that dietary patterns with higher relative to lower intakes of foods (either explicitly or likely) classified as UPF were associated with greater adiposity and/or risk of overweight.^6,9,12,18,28^ Specifically, dietary patterns higher in UPF were associated with significantly greater waist circumference, fat mass index, body fat percentage,^9–11^ BMI or BMIz-score,^9,12,18,28^ weight and/or lower length/height for age z-score,^9,12^ and risk of overweight.^26^ Seven of these studies based UPF categorization on the Nova classification group 4. The amount or contribution of UPF was analyzed differently in each article and included continuously per 100g,^11^ per SD,^26^ per 10%,^10^ or per 100 kcal^28^ increments; by % weight,^9^ or dichotomously as either 1300 kcal vs. 300 kcal^18^ or 6 or more compared to 5 or less Nova 4 sub-groups.^12^ The mean percent of total energy from UPF within dietary patterns consumed ranged from 27% to 42% among the studies reporting that information. One study reported a range of 1 to 27 servings/day from UPF across participants.^7^ One study reported mean energy in kcal/day from UPF as 698 kcal/d.^18^ One study reported the range of UPF items per day from 9 to 15.^13^

The magnitude of effect estimates across the body of evidence varied, but tended to be small (e.g., <10% relative risk). In addition, many of the articles reported both statistically significant results as well as comparisons or findings that did not reach statistical significance. For example, Vedovato and colleagues^28^ found that a dietary pattern higher in UPF (per 100 kcal) at age 4 years, but not at age 7 years, was significantly associated with higher BMI z-score at age 10 years. In contrast, Heerman et al. 2023^18^ observed that a dietary pattern with 1300 vs. 300 kcal from UPF in children at age 3 years or 4 years, but not at age 5 years, was significantly associated with higher BMI z-score at age ~ 6 to 8 years.

- Two articles each examined consumption of dietary patterns that were comprised primarily of foods/items likely classified as UPF.^6,27^ Smith and colleagues^27^ found that the ‘Packed Lunch’ dietary pattern at age 9 years was associated with higher fat mass gains in girls and less lean mass gain in boys at age 11 years (among valid-reporters). Results examining under-reporters were not statistically significant. Arruda and colleagues^6^ found that the ‘Western’, but not the ‘Snacks’ dietary pattern, at age 10 to 14 years was significantly associated with higher BMI z-score at age 13-17 years.
- Two articles from the same cohort examined the ‘Energy-dense foods (EDF)” dietary pattern comprised primarily of foods/items likely classified as UPF (e.g., soft drinks, salty pastry, sweets, processed meats) compared to the ‘Healthier’ dietary pattern (low in EDF components and comprised of non-processed foods such as fruits and vegetables).^14,15^ Consuming the ‘EDF’ v. ‘Healthier’ dietary pattern at age 4 years was significantly associated with statistically higher risk of overweight or obesity, greater fat mass index, BMI z-score, and weight-to-height-ratio in girls; higher risk of overweight/obesity in boys at age 7 years^14^ and higher BMI, fat mass index, weight-to-height-ratio and risk of obesity in girls at age 10 years.^15^ However, no significant associations were found for fat mass percentage in girls or boys at either follow-up, and for most outcomes in boys (BMI z-score, fat mass index, weight-to-height-ratio) at both follow-up points.

Two articles reported that dietary patterns with minimal or no UPF were associated with lower BMI z-score, waist circumference,^7,29^ and fat mass z-score.^29^ Vilela and colleagues^29^ found that consumption of less/minimal UPF (Nova 2+1 per 100g) was significantly associated with lower fat mass z-score, BMI z-score, waist circumference z-score at age 10 years. No significant associations were reported when examining dietary patterns based on Nova 3 classification of foods in relation to outcomes. No significant associations were found between consumption of more UPF (Nova 4 per 100g) and fat mass z-score, BMI z-score, waist circumference z-score at age 10 years. Also, none of the dietary patterns examined in this article were associated with fat-free mass z-score. Bawaked and colleagues^7^ found that consuming less vs. more UPF (medium or low UPF compared to high UPF based on Nova) at age 4 years associated with lower waist circumference at age 7 years, but this was not statistically significant.

One article reported that a dietary pattern higher in UPF was associated with lower BMI and body fat percentage, but complete data were not reported.^13^ Cunha and colleagues^13^ found that consuming more vs. less UPF (Q4 vs. Q1 Nova 4) at mean age 15.7 years was significantly associated with lower BMI and lower body fat percentage after 3-year follow-up. Notably, values and/or data supporting those results were not reported. In addition, total energy intake and BMI at baseline were lower in those with the highest consumption levels of UPF.

Findings that were not statistically significant (or mostly non-significant) between dietary patterns with varying amounts of UPF and outcomes generally supported a similar direction as significant results described above.

- González and colleagues^17^ found that consuming greater amounts of UPF (Nova 4 per 100g) at age 24.4 months was not significantly associated with incidence of obesity at age 47.8 months.
- Saldanha-Gomes and colleagues^25^ reported that consumption of a dietary pattern comprised of many UPF at age 2 years’ was associated with higher risk of early adiposity rebound at age 5.5 years, but this result did not reach statistical significance. In another article by Saldanha-Gomes and colleagues,^24^ consumption of that dietary pattern at age 2 years was not associated with BMI or % body fat at age 5 years.
- Wolters and colleagues^30^ found that consumption of a dietary pattern at age 5-7 years (labelled “Fast-food”) was not associated with BMI, fat mass index, or weight-to-height ratio at age 9-11 years. Change toward greater consumption of that pattern from baseline to follow-up was significantly associated with greater fat mass index at follow-up but not with BMI or weight-to-height ratio. Additionally, consumption of a different pattern at age 5-7 years (labelled, “Snack”) was not associated with fat mass index and weight-to-height ratio, but weakly associated with higher BMI at follow-up 2 years later. Change toward greater consumption of that pattern from baseline to follow-up was not associated with BMI, fat mass index, or weight-to-height ratio at follow-up.
- Biazzi and colleagues^8^ found that consuming “DP II” comprised of foods mostly classified as UPF, at age 7-10 years was not significantly associated with change in BMI z-score at age 12-15 years.
- Gasser and colleagues^16^ found that consuming the ‘Unhealthy’ dietary pattern, comprised of “snacks, sugary drinks, and other UPF”, at age 4-5 years was not significantly associated with BMI z-score or weight-to-height ratio at age 14-15 years. In addition, this dietary pattern at age 2-3 years was not significantly associated with BMI z-score at age 10-11 years, but it was (weakly) associated in some waves with higher weight-to-height ratio at age 10-11 years.
- Hennessy and colleagues^19^ found no significant difference in body weight, weight z-score, height, height z-score, BMI, BMI z-score, prevalence of overweight, prevalence of obesity, prevalence of overweight/obesity, or prevalence of underweight at age 5 years between consumption of the ‘Low Nutrient-Density’ dietary pattern, which was comprised of confectionary, processed meat, and convenience foods compared to the ‘Traditional’ dietary pattern of whole meal breads, fresh meat, and fruit at age 2 years.
- Marks and colleagues^21^ found that consuming a dietary pattern including chips and other snacks, candies, and other UPF, at age 11-13 years was not significantly associated with prevalence of overweight/obesity 1 year later.
- Oellingrath and colleagues^22^ found that consuming a dietary pattern characterized by high-energy processed fast foods, refined grains, cakes and sweets at age 12-13 years was not significantly associated with prevalence of overweight 3 years later in those with healthy weight at baseline, nor in those with overweight at baseline.
- Pala^23^ found that consumption of a dietary pattern comprised of street foods, savory pastries, and chocolate bars (‘Snacking’) or a dietary pattern of chocolate spreads, biscuits and sweets/candy, fried meat, and soft drinks (‘’Sweet’), at age 2-10 years were not associated with risk of overweight/obesity or change in BMI approximately 2 years later.
- Marinho^20^ found no significant association between the EDF pattern described previously (primarily items likely to be UPF such as soft drinks, salty pastry, sweets, processed meats) compared to a ‘Healthier’ dietary pattern (low in EDF components and comprised of non-processed foods such as fruits and vegetables) and waist-to-weight ratio as a mediator of intelligence quotient.

### Conclusion statement and grade

The 2025 Dietary Guidelines Advisory Committee developed a conclusion statement to answer the question based on their review of evidence examining dietary patterns with varying amounts of UPF consumed during childhood and adolescence and measures of growth, body composition, and risk of overweight/obesity (Table 8).

Table 8 Conclusion statement, grades for dietary patterns with varying amounts of ultra-processed food consumed by children and adolescents and growth, body composition, and risk of obesity

Conclusion Statement | Dietary patterns consumed by children and adolescents with higher amounts of foods classified as ultra-processed food are associated with greater adiposity (fat mass, waist circumference, BMI) and risk of overweight. This conclusion statement is based on evidence graded as limited. (Grade: Limited)
Grade | Limited
Body of Evidence | 26 articles from prospective cohort studies
Consistency | Some concerns due to variation in the magnitude and direction of effect estimates
Precision | Serious concerns with relatively smaller sample sizes and wide variance around effect estimates
Risk of bias | Serious concerns due to potential confounding, exposure misclassification, and not accounting for missing data
Directness | Serious concerns that not all of the dietary patterns examined were directly varying in amounts of UPF
Generalizability | Participant characteristics, dietary patterns, and outcomes likely generalize but there were serious concerns with applicability of UPF to the U.S. population given the inconsistencies in amounts and types of UPF available in the countries and time periods included in the studies.

#### Assessment of Evidence

This body of evidence includes studies with both larger and smaller sample sizes as well as null findings, which makes publication bias less likely. As outlined and described below, the body of evidence was assessed for the following elements used when grading the strength of evidence.

##### Consistency

The direction of findings were similar regardless of statistical significance suggesting that dietary patterns higher in foods classified as UPF were associated with a higher risk of overweight and/or greater BMI, waist circumference, and/or fat mass. However, the size of effects ranged widely and confidence intervals often included the null. Only one article reported results in the opposite direction, but those findings were likely explained by methodological inconsistencies.

##### Precision

Studies ranged in analytic sample sizes from n=243 to n=9,427. Several articles had either smaller sample sizes, minimal variability between the exposure and comparator to detect an effect, and/or limited number of events.

##### Risk of bias

Various potential sources of bias were identified (Table 5). Most of the key confounders were accounted for across studies, with exception of race and/or ethnicity of participants. Studies that classified UPF based on a single baseline diet assessment are more prone to misclassification of their usual intake over time, particularly among children. Assessment of foods and beverages as UPF from food-frequency questionnaires has not been validated in all studies and may also contribute to potential exposure misclassification. All of the studies objectively measured the outcomes, but several articles did not account for missing data in the analysis.

##### Directness

Studies using Nova classification of UPF were more direct in addressing the relationship of interest compared to the studies that used factor/cluster/latent class methods for deriving dietary patterns. Studies that used a posteriori methods were not directly intending to examine variation in UPF, but rather examine consumption of dietary patterns comprised of many foods often consumed in highly processed versions and/or likely to be classified as UPF with few exceptions. No studies directly compared dietary patterns with the same types of foods in a non-ultra-processed compared to ultra-processed version.

##### Generalizability

Only one study was conducted in the United States. Socioeconomic position of participants varied across studies and was most commonly based on parental education. Most of the dietary patterns compared and components among the dietary patterns are commonly consumed in the United States, such as cookies, cakes, candy/confectionary, luncheon (cold) meats, nuggets, fish sticks, and sugar-sweetened beverages, with relatively few elements that may be less generalizable such as curry-sausage or muesli. Outcomes were generalizable to those experienced in the United States population.

Table 9 Studies examining the relationship between dietary patterns with varying amounts of ultra-processed food consumed in children and adolescents and growth, body composition and composition and risk of obesity^a^

Article Information | Intervention/exposure and comparator | Results | Methodological considerations
Arruda, 2021 ^6^; PCS; Brazil; N=773; Participant data:; - ~82% non-White, 18% White skin-colour; - 100% Brazilian; - ~50% middle-economic class; 32% maternal education > HS; - Enrolled 6th graders in municipality of Joao Pessoa;; - Excluded those <10 and >14 y, with disability limiting PA or responding to questionnaires, who were pregnant, with lack of anthropometric measurements, lack of 24-h recall data, LFU | Age at dietary pattern: 10 to 14 years; - [underlined: ‘Snacks’:] positively correlated with intake of processed meats, butters and margarines, breads and breakfast cereals, cheeses, and coffee and teas;; - [underlined: ‘Western’]: positively correlated with intake of sweets, pastries, sweetened drinks, cheese; negatively with coffee and teas; Method: Factor/Cluster Analysis | Age at outcome: 13 to 17 years; Results:; BMI z-score; - ‘Snacks’: β=-0.014, 95% CI: −0.033, 0.005; - ‘Western’: β=0.024, 95% CI: 0.001, 0.047 | - Did not account for: Race/ethnicity (Brazilian 6th graders); - Diet assessed with 24-hour recall at baseline, and a 2nd 24-hour recall in 30% of all waves; Outcomes objectively measured in triplicate (via WHO age/sex-specific BMI); - Funding: São Paulo Research Foundation
Bawaked, 2020 ^7^; PCS; Spain; N=1480; 1256 BMI, 1248 WC; Participant data:; - Spanish; - Social class: 24% I/II; 29% III; 47% IV; M. Education: 22% low, 41% 2nd, 36% Uni.; - Included mothers ≥16years old, delivering at referene hospital, Spanish/regional language, singelton pregnanc without assisted conception, children with relevant data (physical activity, sedentary activity, dietary, BMI/WC) | Age at dietary pattern: 4 years; [underlined: “Ultra-processed” food] (UPF, Nova food classification system, group 4 [Monteiro, 2019]) e.g. Carbonated drinks, processed meat, biscuits [cookies], candy [confectionery], ‘instant’ packaged soups and noodles, sweet or savory packaged snacks, and sugared milk and fruit drinks.; Method: Index/Score Analysis | Age at outcome: 7 years; Results:; UPF (High, ref) & BMI z-score; - Med UPF, β: −0.04, 95% CI: −0.15, 0.06; - Low UPF, β: −0.10, 95% CI: −0.20, 0.01; - p=0.07; UPF (High, ref) & Waist circumference; - Med. UPF, β: −0.05, 95% CI:−0.18, 0.07; - Low UPF, β: −0.08, 95% CI: −0.21, 0.04; - p=0.18 | - Did not account for: Race/ethnicity; Physical Activity (modelled as independent variable of interest); TEI; - Diet assessed once via FFQ at age 4 years for past 12 months; Misclassification possible; Outcomes objectively measured; - Funding: Instituto de Salud Carlos III; EU Commission; Generalitat Valenciana; Generalitat de Catalunya-CIRIT; Department of Health of the Basque Government; Provincial Government of Gipuzkoa; Fundació La marató de TV3
Biazzi, 2017 ^8^; PCS; Brazil; N=458 (1158 baseline); Selection/Participant data:; - Income, mo.: 47% <3; 27% 3-5; 15% 5-10; 11% >10; - Excluded those with extreme dietary intake (outlier) | Age at dietary pattern: 7 to 10 years; ‘[underlined: DP II]’: Salty snacks, French fries, fast-food, Sugary beverages; Method: Factor/Cluster Analysis | Age at outcome: 12 to 15 years; Results:; - DP II & Δ BMI z-score, Coefficient: 0.02; Effect size: 0.00, p=0.45 | - Did not account for: Race/Ethnicity; - Diet assessed with 1-day recall questionnaire at baseline and F/U; Outcomes objectively measured by trained staff (BMI z-score via WHO age/sex-specific BMI);; - Accounted for missing data via testing those with F/U v. LFU; - Funding: Brazilian National Council for Scientific and Technological Development
Chang, 2021 ^9^; PCS; United Kingdom; N=9025; Selection/Participant data:; - 90% ‘White’, 9% ‘Non-White’, 2% ‘missing’ ; UK-birth-cohort; - ~30% higher, ~30% intermediate, ~30% lower, 10% missing info on SEC; - Pregnant women with an expected delivery date between April 1991 and Dec. 1992; Excluded those missing dietary data and/or outcome data | Age at dietary pattern: 7 years; [underlined: UPF] (Nova food classification system, group 4 [Monteiro, 2019]) e.g. Soft drinks; sweet or savoury packaged snacks; ice cream, chocolate, candies; massproduced packaged breads and buns; margarines and spreads; cookies, pastries and cake mixes; breakfast cereals and cereal/energy bars; milk, cocoa and fruit drinks; meat and chicken extracts and instant sauces; infant formulas, follow-on milks and other baby products; ready-to-heat/eat products and dishes (pies, pasta, pizza, desserts); processed meats and sausages; packaged soups and noodles; flavoured and/or artificial sweetened yoghurt; Method: Index/Score Analysis | Age at outcome: 24 years; Results: UPF Q1, HR: 0, ref; BMI: Q5 vs. Q1, HR: 1.18, 95% CI: 0.78, 1.57; - Q2, HR: 0.06, 95% CI: −0.10, 0.23; - Q3, HR: 0.006, 95% CI: −0.16, 0.17; - Q4, HR: 0.02, 95% CI: −0.15, 0.19; - Q5, HR: 0.08, 95% CI: −0.09, 0.24; BMI z-score; - Q2, HR: 0.06, 95% CI: −0.01, 0.13; - Q3, HR: 0.03, 95% CI: −0.04, 0.10; - Q4, HR: 0.05, 95% CI: −0.02, 0.12; - Q5, HR: 0.05, 95% CI: −0.02, 0.12; Body fat %: Q5 vs. Q1, HR: 1.53, 95% CI: 0.81, 2.25; - Q1, ref, HR: 0; - Q2, HR: 0.65, 95% CI: −0.01, 1.30; - Q3, HR: 0.67, 95% CI: 0.02, 1.32; - Q4, HR: 1.02, 95% CI: 0.35, 1.67; - Q5, HR: 1.47, 95% CI: 0.81, 2.13; FMI: Q5 vs. Q1, HR: 0.78, 95% CI: 0.46, 1.08; - Q2, HR: 0.08, 95% CI: −0.09, 0.26; - Q3, HR: 0.11, 95% CI: −0.06, 0.28; - Q4, HR: 0.17, 95% CI: −0.01, 0.34; - Q5, HR: 0.27, 95% CI: 0.09, 0.45; Fat mass, kg; - Q2, HR: 0.11, 95% CI: −0.31, 0.52; - Q3, HR: 0.10, 95% CI: −0.32, 0.51; - Q4, HR: 0.20, 95% CI: −0.22, 0.62; - Q5, HR: 0.51, 95% CI: 0.08, 0.93; Lean mass index; - Q2, HR: 0.005, 95% CI: −0.06, 0.07; - Q3, HR: 0.009, 95% CI: −0.06, 0.07; - Q4, HR: −0.01, 95% CI: −0.08, 0.05; - Q5, HR: −0.01, 95% CI: −0.08, 0.05; Lean mass, kg; - Q2, HR: 0.13, 95% CI: −0.16, 0.42; - Q3, HR: −0.01, 95% CI: −0.30, 0.28; - Q4, HR: −0.07, 95% CI: −0.36, 0.23; - Q5, HR: 0.07, 95% CI: −0.23, 0.37; Waist circumference, cm: Q5 vs. Q1, HR: 3.08, 95% CI: 2.08, 4.06; - Q2, HR: 0.26, 95% CI: −0.14, 0.66; - Q3, HR: 0.03, 95% CI: −0.36, 0.42; - Q4, HR: 0.22, 95% CI: −0.18, 0.62; - Q5, HR: 0.16, 95% CI: −0.25, 0.56; Weight, kg: Q5 vs. Q1, HR: 3.66, 95% CI: 2.18, 5.12; - Q2, HR: 0.35, 95% CI: 0.007, 0.69; - Q3, HR: 0.30, 95% CI: −0.03, 0.63; - Q4, HR: 0.34, 95% CI: −0.007, 0.68; - Q5, HR: 0.30, 95% CI: −0.04, 0.65 | - Did not account for: n/a (all accounted for); - Diet assessed with 3-day food diary at multiple points (age 7, 10, 13 years); Outcomes objectively measured by trained staff (BMI z-score calculated/defined via Cole 1990 British Growth charts); - Funding: UK Medical Research Council; Wellcome Trust; University of Bristol
Costa, 2019 ^10^; PCS; Brazil; N=315; Selection/Participant data:; - 57% Non-White; - 100% low SES: 71% ≤ $3,000/y; 35% mothers employed, 89% fathers employed; 56% of mothers/fathers had < 8y education; - Excluded those with HIV+, congenital disease, NICU stays, not from maternity ward of low-income hospital in urban Brazil | Age at dietary pattern: 4 years; [underlined: UPF] (Nova food classification system, group 4 [Monteiro, 2019]) by % TEI contribution: Highest in Sweets (candy, chocolate, ice cream); Breads; Biscuits (crackers and cookies); Soft drinks (soda, sweetened juice and sports drinks); Powdered chocolate; Savory chips and Salty snacks; Processed meat; Sugary Milk beverages; Instant noodles, dehydrated soup, mayonnaise, dressing/sauces; Breakfast cereals (lowest mean intake at age 4y); Method: Index/Score Analysis | Age at outcome: 8 years; Results:; - UPF per 10% & Δ BMI, β: 0.00, 95% CI: −0.02, 0.01; p=0.732; - UPF per 10% & Δ Skinfold thickness, β: 0.04, 95%CI: −0.05, 0.14; p=0.377; - UPF per 10% & Δ Waist circumference, β: 0.06, 95% CI: 0.01, 0.13; p=0.046; - UPF per 10% & Δ Waist-to-Height Ratio, β: 0.00, 95%CI: 0.00, 0.00; p=0.089 | - Did not account for: Age, Race/Ethnicity, Physical activity (did screen time); - Diet assessed with 24-hour recall at 4 and 8 years from self-report with help of parent; Outcomes objectively measured;; - Funding: Brazil National Council for Scientific and Technological Development
Costa, 2021 ^11^; PCS; Brazil; Analytic N=3128; Selection/Participant data:; - 73% ‘white skin colour’; 27% ‘black/brown/yellow/indi genous skin colour’; - maternal education: 16% 0-4y, 41% 5-8y, 33% 9-11y, 10% 12y+; - Newborns in urban Pelotas/Jardim within Gapao do Leao | Age at dietary pattern: 6 years; [underlined: UPF] (Nova food classification system, group 4 [Monteiro, 2019]): Sweet cookies; salty cracker; yogurt or milk drink; ham; mortadella; sausage; butter or margarine; mayonnaise; candies, lollipop or chewing gum; chocolate bar or bonbon; ice cream or popsicle; chocolate powder; sugar sweetened beverages; artificially sweetened beverages (light, diet or zero); artificial juice (powder or box); salty snacks; sandwich cookies; gelatin.; Method: Index/Score Analysis | Age at outcome: 6-11 years; Results:; - UPF & Δ Fat mass index 6-11y: β: 0.14, 95% CI: 0.13, 0.15; p<0.001 (adj. non-UPF); - UPF & Δ Fat mass index 6-11y: β: 0.05, 95% CI: 0.04, 0.06; p<0.001 (adj. TEI) | - Did not account for: Age, birthweight but not anthropometry at baseline (assessed change from 6-11 years as main result); - Diet assessed via FFQ at 6 years (parent-report) and 11 years (parent w/ child help); Misclassification possible; Outcomes objectively measured;; - Moderate effect size per 100g increase in UPF was associated with 0.14 kg/m2 of fat mass index increase from 6 to 11 years; 58% of effect of UPF on fat mass index due to mediation from TEI (42% direct effect UPF); - Funding: Wellcome Trust; Departamento de Cieˆncia e Tecnologia; Conselho Nacional de Desenvolvimento Cientı´fico e Tecnolo´ gico- Brazil
Costa, 2022 ^12^; PCS; Brazil; N=3498; Selection/Participant data:; - 70% ‘white’, 13% ‘brown’, 17% ‘black skin colour’; - Wealth index, ~20% (each Q1 (poorest) through Q5 (richest)); Maternal education mean 10 years (SD: 3.9); - Newborns in urban Pelotas/Jardim within Gapao do Leao | Age at dietary pattern: 2 years; [underlined: UPF] (Nova food classification system, group 4 [Monteiro, 2019]): 9 sub-groups: i) Instant noodles 30%; (ii) Soft drinks 37%; (iii) Chocolate powder (in milk) 43%; (iv) Nuggets, hamburger or sausages 43%; (v) Salty snacks, packaged 46%; (vi) Candies, lollipops, chewing gum, chocolate or jelly 65%; (vii) Cookie (sandwich-type) or Sweet Biscuit 65%; (viii) Juice from can, box, or powder 67%; (ix) Yogurt 88%; Method: Index/Score Analysis | Age at outcome: 4 years; Results:; UPF & BMI-age-z (BAZ), T1, ref; - cont. β: 0.02, 95% CI: 0.01, 0.03; p<0.001; - T2, β: 0.05, 95% CI: −0.01, 0.11; - T3, β: 0.01, 95% CI: −0.06, 0.07; - p=0.207; - 6+ vs. ≤ 5 of 9 sub-groups & BAZ, β: 0.09, 95% CI: 0.04, 0.14; p<0.001; UPF & Length or Height-for-age- z-score, T1, ref; - cont. β: −0.03, 95% CI: −0.04, −0.02; p<0.001; - T2, β: −0.04, 95% CI: −0.08, 0.01; - T3, β: −0.06, 95% CI: −0.11, −0.01; - p=0.023; - Yes or No to 6+ sub-groups, β: −0.10, 95% CI: −0.14, −0.06; p<0.001 | - Did not account for: Age; TEI; - Diet assessed via FFQ at 2 years and 4 years; Misclassification possible (Y/N usually consuming 9 sub-groups); Outcomes objectively measured; Precision when UPF was analyzed continuously; - Funding: Wellcome Trust; Conselho Nacional de Desenvolvimento Cientı´fico e Tecnolo´ gico- Brazil; Fundação de Amparo a Pesquisa do Estado do Rio Grande do Sul; Children’s Pastorate; Bernard van Leer Foundation
Cunha, 2018 ^13^; PCS; Brazil; N=1035; Selection/Participant data:; - Data NR (Brazilian); - Excluded those with pregnancy or physical disability, w/ obesity at baseline; Included 1st year high-school students from 4 private and 2 public urban schools | Age at dietary pattern: 15.7 years, mean (13.5-19.5 years); [underlined: UPF] (Nova food classification system, group 4 [Monteiro, 2019]) e.g. Sodas; Fruit drinks; Candies; Cookies; Chocolate milk beverages; Guarana (soda); Packed fruit juices; Ham; french fries; Sweet Pastries; Chocolate; Chips; Fried, filled rolls; Oven-baked rolls; Instant pasta; Ice cream; Jelly; Nuggets; Hamburger; Pizza; Hot dog; Cheese rolls; Method: Index/Score Analysis | Age at outcome: 16.6 years (14.4-19.8); 17.6 years (15.3-20.9); Results:; - UPF Q4 v. Q1 associated with lower BMI at 3 year F/U (values/data NR);; - No interaction between age and UPF & BMI (p=0.07); Under-reporting of UPF intake (coefficient=-0.94) and PA (coefficient=-1.0) associated with BMI at F/U; - UPF Q4 v. Q1 associated with lower body fat % at 3 years F/U (values/data NR);; - No interaction between age and UPF & body fat % (p=0.07) | - Did not account for: Race and/or ethnicity; SEP; - Diet assessed once via (valid) FFQ; Misclassification possible; Outcomes objectively measured by trained staff; Lower TEI in Q4 of UPF possibly mediated – Q4 v. Q1 of UPF at baseline also had lower BMI & body fat %; - Funding: National Council for Scientific and Technological Development; Research Support Foundation of the State of Rio de Janeiro; Coordination for Improvement of Higher Education Personnel
Durao, 2017 ^14^; PCS; Portugal; N=3473; Selection/Participant data:; - Data NR (Portuguese birth cohort); - Excluded those with diseases that influence diet, missing data | Age at dietary pattern: 4 years; - [underlined: ‘Energy dense foods’ (EDF]): Sweets, soft drinks, salty pastry, processed meat; - [underlined: ‘Healthier’]: higher consumption of fruit, vegetables, vegetable soup, and fish; lower EDF; Method: Latent Class Analysis | Age at outcome: 7 years; Results:; ‘EDF’ v. ‘Healthier’ ref (SS: linear regression coefficient); Overweight/Obesity; - ♀ SS: 1.48, 95 % CI: 0.96, 2.29; - ♂ SS: 3.15, 95 % CI: 1.54, 6.45; BMI; - ♀ SS: 0.074, 95 % CI: 0.002, 0.146; - ♂ SS: 0.021, 95 % CI: −0.055, 0.097; Fat mass, %; - ♀ SS: 0.045, 95 % CI: −0.026, 0.116; - ♂ SS: 0.02, 95 % CI: −0.053, 0.093; Fat mass index; - ♀ SS: 0.078, 95 % CI: 0.011, 0.145; - ♂ SS: 0.029, 95 % CI: −0.040, 0.098; Waist-hip-ratio; - ♀ SS: 0.108, 95 % CI: 0.028, 0.187; - WHR ♂ SS: 0.025, 95 % CI: −0.050, 0.1 | - Did not account for: Race/ethnicity; - Diet assessed once via FFQ at baseline (only validated in adults); Outcomes objectively measured (BMI z-score via WHO age/sex-specific BMI); - Funding: Programa Operacional de Saúde (Regional Department of Ministry of Health); Portuguese Foundation for Science and Technology (FCT) and by the Calouste Gulbenkian Foundation; FEDER from the Operational Programme Factors of Competitiveness—COMPETE and through
Durão, 2022 ^15^; PCS; Portugal; N=1861 ♀; 1962 ♂; Selection/Participant data:; - Data NR (Portuguese birth cohort); - Excluded those with conditions that affect dietary intake, incomplete data at 4y on PA, screen time, or maternal BMI, and no BP data at 10y | Age at dietary pattern: 4 years; - [underlined: ‘Energy dense foods’ (EDF):] Sweets, soft drinks, salty pastry, processed meat; - [underlined: ‘Healthier’:] higher consumption of fruit, vegetables, vegetable soup, and fish; lower EDF; Method: Latent Class Analysis | Age at outcome: 10 years; Results:; ‘EDF’ v. Healthier (OR: 1 ref) and Risk of overweight,; - ♀ OR: 1.48, 95% CI: 0.96, 2.29; - OW, ♂ OR: 1.01, 95% CI: 0.66, 1.53; Risk of obesity,; - ♀ OR: 3.15, 95% CI: 1.54, 6.45; - ♂ OR: 1.16, 95% CI: 0.62, 2.18; BMI; - ♀, β: 0.074, 95% CI: 0.002, 0.146; - ♂, β: 0.021, 95% CI: −0.055, 0.097; Fat mass, %; - ♀, β: 0.045, 95% CI: −0.026, 0.116; - ♂, β: 0.020, 95% CI: −0.053, 0.093; Fat mass index; - ♀ β: 0.078, 95% CI: 0.011, 0.145; - ♂ β: 0.029, 95% CI: −0.040, 0.098; Waist-hip-ratio; - ♀ β: 0.108, 95% CI: 0.028, 0.187; - WHR ♂ β: 0.025, 95% CI: −0.050, 0.100 | - Did not account for: Race/ethnicity; - Diet assessed once via FFQ at baseline (only validated in adults); Outcomes objectively measured (BMI z-score via WHO age/sex-specific BMI); - Funding: Health Operational Programme–Saúde XXI, Community Support Framework III, Regional Department of Ministry of Health, FEDER– COMPETE, the Foundation for Science and Technology–FCT, a Researcher Contract, Epidemiology Research Unit and Laboratory
Gasser, 2019 ^16^; PCS; Australia; N=2009 to 2014; Selection/Participant data:; - 4-5% Indigenous Australian; - Socioeconomic Index: 13-19% Q1 (richest), 17-18% Q2, 20% Q3, 21% Q4, 23% Q5 (poorest); - All participants were enrolled in Australia’s Medicare database | Age at dietary pattern: 2 to 3 years, B cohort; 4 to 5 years, K cohort; ‘[underlined: Unhealthy’:] Positive: savoury snacks and sweetened drinks in all waves; meat pies, hamburgers, hot dogs, sausages or sausage rolls, hot chips and fruit juice in most waves; sugary foods, diet drinks, energy drinks, coffee and soya milk products mainly in the later waves; Negative: water in six of the eleven waves; Method: Factor/Cluster Analysis | Age at outcome: 10 to 11 years, B Cohort; 14 to 15 years K Cohort; Results:; BMI z-score; K cohort,; - Wave (W) 2, β: −0.01, 95% CI: −0.04, 0.02; p-trend=0.47; - W 3, β: −0.01, 95% CI: −0.04, 0.02; p-trend=0.42; - W4, β: 0.01, 95% CI: −0.02, 0.03; p-trend=0.52; - W5, β: 0.01, 95% CI: −0.03, 0.04; p-trend=0.73; B cohort,; - W2, β: 0.02, 95% CI: −0.03, 0.06; p-trend=0.46; - W3, β: 0.01, 95% CI: −0.03, 0.05; p-trend=0.54; - W4, β: 0.02, 95% CI: −0.01, 0.05; p-trend=0.24; - W5, β: 0.01, 95% CI: −0.02, 0.05; p-trend=0.37; Weight-to-Height ratio K cohort,; - W2, β: −0.01, 95% CI: −0.04, 0.02; p-trend=0.47; - W3, β: −0.02, 95% CI: −0.06, 0.02; p-trend=0.40; - W4, β: −0.03, 95% CI: −0.06, −0.00; p-trend=0.03; - W5, β: −0.05, 95% CI: −0.09, −0.00; p-trend=0.03; B cohort,; - W2, β: 0.01, 95% CI: −0.03, 0.05; p-trend=0.62; - W3, β: 0.04, 95% CI: 0.00, 0.07; p-trend=0.03; - W4, β: 0.03, 95% CI: 0.00, 0.06; p-trend=0.03; - W5, β: 0.04, 95% CI: 0.00, 0.07; p-trend=0.03 | - Did not account for: n/a (all accounted for); - Diet assessment at multiple times using non-validated tool; Outcomes objectively measured by trained staff; Derived dietary pattern scores for each child at each wave (0-1 years B-Cohort; 4-5 years K Cohort);; - Funding: Department of Social Services, Australian Institute of Family Studies, Australian Bureau of Statistics
González, 2023 ^17^; PCS; Brazil; Uruguay; N=6468; 2550 (ENDIS), 3918 (Pelotas); Selection/Participant data:; - NR (all Latin-American); - Education: 48% of mothers had 6-12y; - ENDIS cohort: included children <4 y at baseline with complete data; - Pelotas cohort: children recruited at birth; included those wih two BMI measurements | Age at dietary pattern: 2 years (~25 months); [underlined: UPF] (Nova food classification system, group 4 [Monteiro, 2019]) main sources: Cookies; Packaged dairy deserts; Sweetened Drinks; Cookies; Processed Meat products; Method: Index/Score Analysis | Age at outcome: 4 years (~48 months); Results:; UPF (baseline and current) & Incident Obesity, RR: 1.02, 95% CI: 0.93, 1.12; p=0.680 | - Did not account for: Physical activity; Race/Ethnicity (‘Latin-American’); - Diet assessed once with 24-hour recall (wave 1 ENDIS) or FFQ (wave 2 ENDIS, Pelotas); Different diet assessment methods between waves & cohorts and UPF intake based on FFQ; Outcomes objectively measured; - Funding: National Agency of Investigation and Innovation; Wellcome Trust; Conselho Nacional de Desenvolvimento Cientı´fico e Tecnolo´ gico- Brazil; Fundação de Amparo a Pesquisa do Estado do Rio Grande do Sul; Children’s Pastorate
Heerman, 2023 ^18^; PCS; United States; N=595; Selection/Participant data; - 91.3% Hispanic; 8.7% Non-Hispanic; - 57.5% food secure; 42.5% food insecure;; - 88% use WIC/SNAP, 12% do not use WIC/SNAP;; - Enrolled parent-child pairs qualified for ≥ 1 under-served population service (e.g., WIC), normal to overweight/obesity (BMI 50^th^-95^th^ %tile); spoke English/Spanish; telephone access; free of medical conditions precluding PA | Age at dietary pattern: 4.3 years, mean; 3 to 5 years; [underlined: UPF] (Nova food classification system, group 4 [Monteiro, 2019]) e.g. Soft drinks; sweet or savoury packaged snacks; ice cream, chocolate, candies; massproduced packaged breads and buns; margarines and spreads; cookies, pastries and cake mixes; breakfast cereals and cereal/energy bars; milk, cocoa and fruit drinks; meat and chicken extracts and instant sauces; infant formulas, follow-on milks and other baby products; ready-to-heat/eat products and dishes (pies, pasta, pizza, desserts); processed meats and sausages; packaged soups and noodles; flavoured and/or artificial sweetened yoghurt; Method: Index/Score Analysis | Age at outcome: ~6 to 8 years (F/U 36 months); Results:; UPF high v. low & BMI z-score; - 3 year olds: 1.2, 95% CI: 0.5, 1.9; p<0.001; - 4 year olds: 0.6, 95% CI: 0.2, 1.0; p=0.007; - 5 year olds: −0.1, 95% CI: −0.6, 0.4; p=0.7; - All (ages 3 to 5 years): 0.4, 95% CI: −0.02, 0.7; p=0.07 | - Did not account for: Anthropometry at baseline (tested BMIz); - Diet assessed once with 24-hour-recall; mean daily calories from UPF in sample >60%; Outcomes objectively measured (BMIz via WHO age/sex-specific BMI); mean daily calories from UPF in sample >60%; - Funding: NHLBI
Hennessy, 2023 ^19^; PCS; Ireland; N=375; Selection/Participant data; - 99% Caucasian; - 89% 3rd -level education; 96% married or living with partner; - Included low-risk, nulliparious with singleton <15wk gestation | Age at dietary pattern: 2 years; - [underlined: ‘Low Nutrient Density’ (LND]): confectionary, processed meat, convenience foods; - [underlined: ‘Traditional’]: wholemeal breads, butter, fresh meat, fruit; Method: Factor/Cluster Analysis | Age at outcome: 5 years; Results: ‘LND’ v. ‘Traditional’ dietary pattern:; - %Overweight/Obesity, WHO: 1.1 v. 4.7%; - % Overweight, IOTF: 9.5 v. 11.3%; - % Obesity, IOTF: 1.1 v. 0.9%; - % Underweight, IOTF: 3.2 v. 3.8%; - BMI, mean [SD] (kg/m2): 16 [1.3] v. 16 [1.3]; - BMI z-score, mean [SD]: 0.2 v. 0.3 [0.9]; - Weight [SD], kg: 19.4 [2.3] v. 19.6 [2.4]; - Weight-z [SD]: 0.2 [0.9] v. 0.3 [0.9]; - Height [SD], cm: 110.2 [4.1] v. 110.4 [4.3]; - Height, z-score: 0.1 [0.9] vs. 0.1 [0.9] | - Did not account for: Age, Physical activity, SEP (89% 3rd); - Diet assessed once (baseline) with 2-day weighed, record; Outcomes objectively measured (IOTF and WHO); - Funding: Irish Dept. of Agriculture, Food and the Marine; National Children’s Research Centre
Marinho, 2022 ^20^; PCS; Portugal; N=3575; Participant characteristics:; - Data NR (Portuguese birth cohort); - Excluded pre-term children, children with a disease influencing dietary intake or congenital anomalies, children with characteristics that influence cognitive assessment, and missing data | Age at dietary pattern: 4 years; - [underlined: ‘Energy-dense foods (EDF])’: high intakes of sweets, sugar-sweetened beverages, savory pastry, and processed meat.; - [underlined: ‘Healthier’:] higher consumption of fruit, vegetables, vegetable soup, and fish, with a lower consumption of EDF; Method: Factor/Cluster Analysis | Age at outcome: 10 years; Results:; Weight-to-waist ratio, from mediation to IQ; - Full Scale IQ: β: 0.032, 95% CI: −0.015, 0.082; - Performance IQ: β: 0.032, 95% CI: −0.017, 0.079; - Verbal IQ: β: 0.032, 95% CI: −0.017, 0.087; - Processing Speed IQ: β: 0.032, 95% CI: −0.021, 0.092 | - Did not account for: Anthropometry at baseline, Age, Race/Ethnicity (100% Portuguese birth cohort); - Diet assessed once via FFQ at age 4 years, tested agains 3-day diaries in sub-sample; Misclassification possible due to UPF intake based on FFQ; Outcomes objectively measured, calculated and defined via WHO; Indirect design (IQ main outcome) via mediation analysis of DP & adiposity impacting IQ; - Funding: Health Operational Programme - Saúde XXI, Community Support Framework III and the Regional Department of Ministry of Health, Calouste Gulbenkian Foundation, by FEDER from Operational Programme Factors of Competitiveness, Epidemiology Research Unit
Marks, 2015 ^21^; PCS; Australia; N=243; Selection/Participant data; - 85% Austrailian-born; No significant differences by ehtnicity were found; - Enrolled schools only from bottom-2 of SES strata | Age at dietary pattern: 11 to 13 years, mean 12.2 years; [underlined: Non-core food score] [Marks, 2015], Positive: potato chips or a similar snack; chocolate; lollies (candy); muesli or fruit bars; savory biscuits; sweet biscuits; ice cream; hot chips (french fries); pies, pasties, or sausage rolls; hot dogs; pizza; Method: Index/Score Analysis | Age at outcome: mean, 12.7 years (F/U 1 year); Results:; Non-core food score & Overweight/Obesity: Mean difference: −0.6, 95% CI: −1.7 to 0.5; p=0.26 | - Did not account for: Anthropometry at baseline (within outcome), Physical Activity, SEP (although all bottom 2 SES strata); - Diet assessed twice from questionnaire; Outcomes objectively measured (BMI z-score via WHO);; - Indirectly designed to examine obesity-related behaviors and change of school; - Funding: Windermere Foundation
Oellingrath, 2017 ^22^; PCS; Norway; N=393; Selection/Participant data; - Income: both parents low 7%, one parent/mid 45%, both parents high 46%, missing 2%;; - Education: 52% maternal education uni/college; 40% paternal education uni/college, missing 5% | Age at dietary pattern: 12 to 13 years, mean 12.7; [underlined: ‘Junk Convenient’]: characterised by high-energy processed fast foods, refined grains, cakes and sweets; Method: Factor/Cluster Analysis | Age at outcome: F/U: 3 years; Results:; ‘Junk Convenient’ (T1 ref) & risk of overweight at 10th grade:; - If normal-Weight @ baseline: T2+T3, OR: 0.9, 95% CI: 0.4, 2.3; - If overweight at baseline: T2+T3, OR: 2.2, 95% CI: 0.6, 8.6 | - Did not account for: Race/Ethnicity (Norwegian); - Diet assessed via FFQ (valid) at 7^th^ and 10^th^ grade; Outcomes objectively measured (BMI categories via IOTF); Dieatary pattern combined with physical activity reduced odds of overweight, but only in those already overweight; - Funding: Research Council of Norway and the Public Health Programme for Telemark
Pala, 2013 ^23^; PCS; Italy, Estonia, Cyprus, Belgium, Sweden, Hungary, Germany, Spain; Analytic N=9427; Selection/Participant data; - 15% from Italy, 11% Estonia, 11% Cyprus, 12% Belgium, 12% Sweden, 13% Germany, 17% Hungary, 10% Spain; - Excluded those with missing data | Age at dietary pattern: 2 to 10 years; - [underlined: ‘Snacking’:] Positive loadings for Hamburger, hot dog, kebab, falafel; Butter or margarine on bread, savory pastries, chocolate/candy bars, white bread; Negative: cooked vegetables; - [underlined: ‘Sweet Fat’]: Positive loadings for chocolate or nut-based spreads; Cakes, puddings, cookies; Candy and sweets (no chocolate); fried meat; soft drinks with added sugar or diet; mayonnaise and similar; cured meat and sausages; Method: Factor/Cluster Analysis | Age at outcome: 4 to 12 years; Results:; ‘Snacking’ T1, ref 1; - Overweight/Obesity, T2, OR: 1.09, 95% CI: 0.88, 1.35; - Overweight/Obesity, T3, OR: 1.18, 95% CI: 0.91, 1.52; p-trend=0.22; - Overweight/Obesity, per-unit, OR: 1.03, 95% CI: 0.97, 1.09; - ΔBMI T1, 0.73; - ΔBMI T2, 0.76; p=0.51; - ΔBMI T3, 0.78; p=0.35; - p-trend=0.36; ‘Sweet and fat’ T1, ref 1; - Overweight/Obesity, T2, OR: 1.08, 95% CI: 0.88, 1.33; - Overweight/Obesity, T3, OR: 0.97, 95% CI: 0.77, 1.22; p-trend=0.74; - ΔBMI T1, 0.73; - ΔBMI T2, 0.76; p=0.55; - ΔBMI T3, 0.78; p=0.26; - p-trend=0.26 | - Did not account for: Race/ethnicity (Country); - Diet assessed once at baseline; Water intake was imputed;; - Did not account for missing data; - Funding: European Community’s Sixth RTD Framework Programme
Saldanha-Gomes, 2017 ^24^; PCS; France; Analytic N=883; Selection/Participant data:; - French-birth-cohort; - Household income: ~10% <1500/mo, ~12% > 3800; Maternal Education: ~20% < high-school, ~36-39% 3 year college degree; - Excluded those with multiple pregnancy, diabetes history, French illiteracy, or with plans to move | Age at dietary pattern: 2 years; [underlined: ‘Processed, fast foods’]: high freqency of French fries, processed meat, carbonated soft drinks, crisps, biscuits, pizzas, fruit juices, dairy puddings and ice cream, legumes, and bread; low in cooked vegetables; Method: Factor/Cluster Analysis | Age at outcome: 5 years; Results:; - ♂ BMI −0.04, 95% CI: −0.11, 0.04; P=0.364; - ♀ BMI 0.08, 95% CI: −0.01, 0.17; P=0.099; - ♂ Body fat %, 0.02, 95% CI: −0.20, 0.25; P=0.829; - ♀ Body fat %, 0.19, 95% CI: −0.08, 0.46; P=0.176 | - Did not account for: Race/Ethnicity; - Diet assessed once via FFQ at age 2 years; Outcomes objectively measured (BMI z-score via IOTF); Complete-case analysis produced similar/consistent results as main findings; Cohort participants generally from higher SEP than rest of France; - Funding: Foundation for Medical Research, National Agency for Research, National Institute for Research in Public Health^*^; * Additional funding reported in Saldanha-Gomes et al. 2017 and 2022: French Ministry of Health, French Ministry of Research, INSERM Bone and Joint Disease National Research, Human Nutrition National Research Programs, Paris-Sud University, Nestle, French National Institute for Population Health Surveillance (InVS), French National Institute for Health Education (INPES), the European Union FP7 programmes, Diabetes National Research Program, French Agency for Environmental Health Safety, Mutuelle G´en´erale de l’Education Nationale, French national agency for food security, French-speaking association for the study of diabetes and metabolism
Saldanha-Gomes, 2022 ^25^; PCS; France; Analytic N=1138; Selection/Participant data:; - French-birth-cohort; - 24% 2y university degree; 39% ≥3y university degree; - Excluded children who died, dropped out, 2 year questionnaire not returned, age at adiposity rebound not calculable | Age at dietary pattern: 2 years; [underlined: ‘Processed, fast foods’]: high intakes of French fries, processed meat, carbonated soft drinks, crisps, biscuits, pizzas, fruit juices, dairy puddings and ice cream, legumes, and bread; low in cooked vegetables.; Method: Factor/Cluster Analysis | Age at outcome: 5.5 years, mean; Results:; Early adiposity rebound (AR):; - AR (♂ 3.8 years; ♀3.6 years): OR: 1.23, 95% CI: 1.00, 1.50; p=0.051; - AR cont. in days: β: −24, 95% CI: −55, 8); p=0.14 | - Did not account for: Race/Ethnicity; - Diet assessed once via FFQ at age 2 years; Outcomes objectively measured; Cohort participants generally from higher SEP than rest of France; - Funding: Foundation for medical research, National Agency for Research, National Institute for Research in Public Health^*^
Sirkka, 2021 ^26^; PCS; Netherlands; Analytic N=938; Selection/Participant data:; - Dutch-birth-cohort;; - 28.6% low maternal education; - Excluded those with incomplete dietary and covariate data; no BMI measurement age 3 to 10 years; LFU | Age at dietary pattern: 3 years; [underlined: UPF] pattern characterized by: high intakes of white bread, crisps, savory snacks, and SSB; low intakes of whole-grain bread; Method: Factor/Cluster Analysis | Age at outcome: 10 years; Results:; UPF & Risk of Overweight: OR: 1.30, 95% CI: 1.08, 1.57; p=0.006 | - Did not account for: Physical activity; - Diet assessed once via FFQ at age 3 years (validated in 4-6 years); Outcomes objectively measured (BMI z-score calculated and defined via WHO); - Funding: Unrestricted grant of Hutchison Whampoa Ltd., Hong Kong, and supported by the University of Groningen, Well Baby Clinic Foundation Icare, Noordlease, Paediatric Association Of The Netherlands, Youth Preventive Health Care Drenthe, and the European Union’s
Smith, 2014 ^27^; PCS; United Kingdom; Analytic N=3911; Selection/Participant data:; - 97% ‘White’; 3% ‘Non-White’; UK birth-cohort; - 18% maternal education post-high school; - Excluded those with missing data; other reasons NR | Age at dietary pattern: 9 years; [underlined: ‘Packed Lunch’]: Higher loadings for low-fiber bread, margarine, cheese, cold meats, salty flavorings such as yeast extract, diet squash (dilutable soft drink); Method: Factor/Cluster Analysis | Age at outcome: 11 years; Results: SS, linear regression coefficient; In valid reporters:; Fat mass,; - ♂ SS: 0.989, 95% CI: 0.976,1.002; - ♀ SS: 0.989, 95% CI: 0.978,1; Lean mass; - ♂ SS: 1.003, 95% CI: 1.001,1.005; - ♀ SS: 1, 95% CI: 0.998,1.003; In under reporters:; Fat mass; - ♂ SS: 0.987, 95% CI: 0.968, 1.007; - ♀ SS: 1, 95% CI: 0.983,1.018; Lean mass; - ♂ SS: 0.999, 95% CI: 0.996,1.002; - ♀ SS: 1.001, 95% CI: 0.996,1.005 | - Did not account for: n/a (all accounted for); - Diet assessed once via 3-day diet diary (24 hour recall if diary missed); Outcomes objectively measured (DXA);; - Diet assessments had unclear timing, validity, and reliability in relation to outcomes; Did not account for missing data; - Funding: The UK Medical Research Council, the Wellcome Trust and the University of Bristol; World Cancer Research Fund
Vedovato, 2021 ^28^; PCS; Portugal; Analytic N=1175; Selection/Participant data:; - Portuguese birth cohort; - ~12 years, mean maternal education; 92% children live with both parents; - Excluded those w/o 2-day food diaries; missing data; congenital anomalies or diseases that might influence dietary intake; twins | Age at dietary pattern: 4 years; 7 years; [underlined: UPF] (Nova food classification system, group 4 [Monteiro, 2019]) e.g. Soft drinks; sweet or savoury packaged snacks; ice cream, chocolate, candies; massproduced packaged breads and buns; margarines and spreads; cookies, pastries and cake mixes; breakfast cereals and cereal/energy bars; milk, cocoa and fruit drinks; meat and chicken extracts and instant sauces; infant formulas, follow-on milks and other baby products; ready-to-heat/eat products and dishes (pies, pasta, pizza, desserts); processed meats and sausages; packaged soups and noodles; flavoured and/or artificial sweetened yoghurt; Method: Index/score | Age at outcome: 10 years; Results:; UPF & BMI z-score:; - Age 4 years, β: 0.028, 95% CI: 0.006, 0.051; - Age 7 years, β: 0.014, 95% CI: −0.007, 0.036 | - Did not account for: Race/Ethnicity (100% Portugese-birth cohort); - Diet assessed ≥twice with 2-day or 3-day food diaries at age 4 years and 7 years; Outcomes objectively measured (BMIz via WHO);; - Data NR for sensitivity analyses by UPF in % TEI (only per 100 kcal); - Funding: Portuguese Ministry of Education and Science; Health Operational Programme; Community Support Framework III; Regional Department of Ministry of Health
Vilela, 2022 ^29^; PCS; Portugal; Analytic N=3034; Participant data:; - Portuguese birth cohort; - maternal education, mean 11 years; - Excluded those with missing diet/anthro data; twins; and those with congenital anomalies or diseases impacting food intake | Age at dietary pattern: 7 years; [underlined: UPF] (Nova food classification system, group 4 [Monteiro, 2019]) e.g. Carbonated beverages, fruit-based beverages, other sugar-sweetened beverages; flavored and/or artificial sweetened yoghurt and milk based drinks; sweet or savory packaged snacks; ice-cream, chocolate, candies; mass-produced packaged breads, buns; margarines, spreads; ultra-processed cheeses; cookies, pastries, cake mixes; breakfast cereals, cereal/energy bars; milk/cocoa/fruit drinks; meat and chicken extracts, instant sauces; infant formulas, follow-on milks, other baby products; ready-to-heat/eat products and dishes (pies, pasta, pizza, desserts); processed meats, sausages; packaged soups, noodles; food supplements, artificial sweeteners.; [underlined: Nova 3]: Canned or bottled vegetables, fruits, legumes; salted or sugared nuts, seeds; salted, cured, or smoked meats (e.g., bacon, typical Portuguese sausages); canned fish; fruits in syrup; cheeses, unpackaged freshly made bread; plain yoghurt with added sugar.; [underlined: Nova 2 + 1:] Butter and lard, vegetable oil, vinegar, honey, table sugar (honey, molasses, syrups) and salt + Fresh, chilled, frozen, dried, vacuum-packed fruits, vegetables, fungi, tubers, roots, grains, legumes; unsalted nuts and seeds; fresh, dried, chilled, frozen meats, poultry and seafood; eggs; fresh and pasteurized milk, plain yoghurt with no added sugar or food additives added; 100% unsweetened fruit juices and smoothies; coffee; tea; water.; Method: Index/Score Analysis | Age at outcome: 10 years; Results:; UPF, Nova 4; - BMI z-score, β:−0.009, 95% CI: −0.029, 0.011; - Fat mass z-score, β:−0.006, 95% CI: −0.022, 0.011; - Fat free mass z-score, β:0.012, 95% CI: −0.005, 0.029; - Waist circumference z-score, β:−0.003, 95% CI: −0.019, 0.014; Nova 3; - BMI z-score, β:0.010, 95% CI: −0.040, 0.061; - Fat mass z-score, β:−0.002, 95% CI: −0.043, 0.040; - Fat free mass z-score, β:0.037, 95% CI: −0.005, 0.079; - Waist circumference z-score, β:0.005, 95% CI: −0.037, 0.046; Nova 2+1; - BMI z-score, β:−0.028, 95% CI: −0.043; −0.014; - Fat mass z-score, β:−0.023, 95% CI: −0.035; −0.011; - Fat free mass z-score, β: 0.002, 95% CI: −0.010, 0.014; - Waist circumference z-score, β:−0.020, 95% CI: −0.032; −0.008 | - Did not account for: Age, Race and/or Ethnicity (Portuguese birth-cohort); - Diet assessed once with 3-day food diaries at age 7 years; Outcomes objectively measured; - Funding: FEDER via the Operational Programme Factors of Competitiveness; Foundation for Science and Technology; Unidade de Investigaç~ao em Epidemiologia - Instituto de Saúde Pública da Universidade do Porto (EPIUnit); the Laboratorio para a Inve
Wolters, 2018 ^30^; PCS; Germany; N=312 Identification and prevention of Dietary- and lifestyle-induced health EFfects In Children and infantS (IDEFICS); N=372 the Kiel Obesity Prevention Study (KOPS); Participant data:; - Low-income, 8% KOPS, 17% IDEFICS;; - Parent Education at least 12y: 58% KOPS, 50% IDEFICS | Age at dietary pattern: 5 to 7 years KOPS; 2 to 9.9 years IDEFICS; - [underlined: KOPS PCA 1 ‘Fast food’]: High loadings for fish sticks, curry-sausage, lasagna, pancakes, potato fritters, pizza, meatballs; - [underlined: KOPS ∆PCA1]: Increased meatballs, fish sticks, lasagna, pizza, pancakes, curry-sausage, potato fritters; - [underlined: IDEFICS PCA 1 ‘Snack’]: High loadings for sweet snacks, potatoes; ketchup etc.; savory snacks; sweetened drinks; chocolate, candy bars; candies, ice cream/milk/fruitbars; - [underlined: IDEFICS ∆PCA3 twd PCA1: Increased sweet snacks, candies, ice cream/milk/fruit-bars, savory snacks; chocolate, candy bars]; Method: Factor/cluster analysis | Age at oucome: 9 to 11 years (KOPS); 4 to 11.9 years (IDEFICS); Results: T1, OR: 1 ref; BMI; - KOPS-PCA1; ○ T2, OR: 0.81, 95% CI: 0.44, 1.49; ○ T3, OR: 1, 95% CI: 0.55, 1.80; ○ Cont., OR: 1.01, 95% CI: 0.95, 1.07; ○ p=0.8457; - KOPS ΔPCA 1; ○ T2, OR: 0.95, 95% CI: 0.51, 1.75; ○ T3, OR: 1.49, 95% CI: 0.83, 2.68; ○ Cont., OR: 1.05, 95% CI: 0.99, 1.10; ○ p=0.1133; - IDEFICS, PCA1; ○ T2, OR: 0.67, 95% CI: 0.35, 1.26; ○ T3, OR: 0.47, 95% CI: 0.23, 0.91; ○ Cont., OR: 0.94, 95% CI: 0.87, 1.01; ○ p=0.081; - IDEFICS, ΔPCA 3; ○ T2, OR: 1.6, 95% CI: 0.83, 3.15; ○ T3, OR: 1.46, 95% CI: 0.75, 2.87; ○ Cont., OR: 1.02, 95% CI: 0.94, 1.11; ○ p=0.6363; Fat mass index; - KOPS-PCA1; ○ T2, OR: 0.67, 95% CI: 0.37, 1.24; ○ T3, OR: 0.73, 95% CI: 0.41, 1.33; ○ Cont., OR: 0.99, 95% CI: 0.94, 1.06; ○ p=0.8556; - KOPS-ΔPCA 1; ○ T2, OR: 1.19, 95% CI: 0.64, 2.21; ○ T3, OR: 1.86, 95% CI: 1.03, 3.38; ○ Cont., OR: 1.06, 95% CI: 1.00, 1.12; ○ p=0.0411; - IDEFICS, PCA1; ○ T2, OR: 1.06, 95% CI: 0.55, 2.03; ○ T3, OR: 0.78, 95% CI: 0.39, 1.52; ○ Cont., OR: 0.98, 95% CI: 0.91, 1.05; ○ p=0.6013; - IDEFICS, ΔPCA3; ○ T2, OR: 1.27, 95% CI: 0.65, 2.50; ○ T3, OR: 1.49, 95% CI: 0.78, 2.90; ○ Cont., OR: 0.99, 95% CI: 0.91, 1.08; ○ p=0.8546; Waist-hip ratio; - KOPS-PCA1; ○ T2, OR: 0.54, 95% CI: 0.29, 1.01; ○ T3, OR: 0.88, 95% CI: 0.49, 1.57; ○ Cont., OR: 1, 95% CI: 0.95, 1.06; p=0.9329; - KOPS-ΔPCA 1; ○ T2, OR: 0.79, 95% CI: 0.43, 1.46; ○ T3, OR: 1.35, 95% CI: 0.76, 2.40; ○ Cont., OR: 1.02, 95% CI: 0.97, 1.08; ○ p=0.3665; - IDEFICS, ΔPCA3; ○ T2, OR: 1.17, 95% CI: 0.59, 2.33; ○ T3, OR: 1.64, 95% CI: 0.86, 3.19; ○ Cont., OR: 1.03, 95% CI: 0.95, 1.12; ○ p=0.4342 | - Did not account for: Race/Ethnicity (adjusted for migration in IDEFICS); - Diet change assessed via FFQ (different in KOPS and IDEFICS) at beginning and end of primary school periods; - Outcomes objectively measured in both cohorts (BMI via IOTF); - Funding: Federal Ministry of Education and Research; Open Access Fund of the Leibniz Association; Additional funding for KOPS and IDEFICS studies separate

a Abbreviations: DXA, Dual-energy X-ray absorptiometry; FFQ, Food frequency questionnaire; F/U, Follow-up; IOTF, International Obesity Task Force; LFU, lost to follow-up; NR, not reported; OR, odds ratio; Q, quantile; SEP/SES, Socioeconomic position/status; T, tertile; T2D, Type 2 Diabetes; UPF, Ultra-processed food; WHO, World Health Organization; ♂ male; ♀ female

Table 10 Risk of bias for observational studies examining dietary patterns with varying amounts of ultra-processed food consumed by children and adolescents and growth, body composition and risk of obesity^a^

Article | Confounding | Exposure classification | Participant Selection | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall
Arruda, 2021^6^ | Low | Some concerns | Low | Low | High | Low | Low | Some concerns
Bawaked, 2020^7^ | High | Low | Some concerns | Low | Low | Low | Some concerns | High
Biazzi, 2017^8^ | Some concerns | Low | Some concerns | Low | Some concerns | Low | Some concerns | High
Chang, 2021^9^ | Low | Some concerns | Some concerns | Low | Some concerns | Low | Some concerns | Some concerns
Costa, 2019^10^ | High | Low | Some concerns | Low | Low | Low | Some concerns | High
Costa, 2021^11^ | Some concerns | High | Low | Low | Low | Low | Low | High
Costa, 2022^12^ | Some concerns | High | Low | Low | Low | Some concerns | Some concerns | High
Cunha, 2018^13^ | High | High | Some concerns | Low | Low | Low | Low | High
Durao, 2017^14^ | Some concerns | Some concerns | Low | Low | High | Low | Some concerns | High
Durão, 2022^15^ | Some concerns | Some concerns | Some concerns | Low | Some concerns | Low | Some concerns | High
Gasser, 2019^16^ | Low | Some concerns | Low | Low | Some concerns | Low | Some concerns | Some concerns
González, 2023^17^ | Some concerns | Very High | Low | Low | Low | Low | High | Very High
Heerman, 2023^18^ | High | Some concerns | High | Low | Low | Low | Some concerns | High
Hennessy, 2023^19^ | High | High | Some concerns | Low | High | Low | Some concerns | High
Marinho, 2022^20^ | Very High | Some concerns | Low | Low | Low | Low | High | Very high
Marks, 2015^21^ | High | High | High | Low | Some concerns | Low | Low | High
Oellingrath, 2017^22^ | Some concerns | Low | Some concerns | Low | High | Some concerns | Some concerns | High
Pala, 2013^23^ | Some concerns | Low | Low | Low | High | Low | Some concerns | High
Saldanha-Gomes, 2017^24^ | Some concerns | Some concerns | Low | Low | Low | Low | Low | Some concerns
Saldanha-Gomes, 2022^25^ | Some concerns | High | Low | Low | Some concerns | Low | Low | High
Sirkka, 2021^26^ | High | Some concerns | Some concerns | Low | High | Low | Low | High
Smith, 2014^27^ | Low | Low | Some concerns | Low | Very High | Low | Some concerns | Very High
Vedovato, 2021^28^ | Low | Some concerns | Low | Low | Some concerns | Low | Some concerns | Some concerns
Vilela, 2022^29^ | Low | Low | Some concerns | Low | Low | Low | Some concerns | Some concerns
Wolters, 2018^30^ | Some concerns | Low | Low | Low | High | Low | Low | High

a Possible ratings of low, some concerns, high, very high, not applicable, or no information determined using the “Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)” tool ( ROBINS-E Development Group, Higgins J, Morgan R, Rooney A . Risk Of Bias In Non-randomized Studies - of Exposure (ROBINS-E). Launch version, 1 June 2022. Available from: https://www.riskofbias.info/welcome/robins-e-tool. ) *Low risk of bias except for concerns about uncontrolled confounding.

## Adults and older adults

Sixteen articles met inclusion criteria that examined the relationship between dietary patterns with varying amounts of UPF consumed by adults and older adults and body composition and risk of obesity (also see Table 8). One article came from an RCT^32^ and 15 came from prospective cohort studies.^31,33–46^

### Description of the evidence

#### Population

Studies were conducted in the following countries: Australia; Brazil (n=4); China; France; Iran; Korea; Spain (n=4); and the United Kingdom (n=2). One study was conducted across multiple countries (Denmark, France, Germany, Greece, Italy, Netherlands, Norway, Spain, Sweden, and the United Kingdom). Two included articles were based on data from the same cohort study but examined dietary patterns differently (e.g., per 100g vs. per 100 kcal increase). Studies ranged in sample size from 661 participants to 348,748 participants.

In 9 articles, the mean BMI of the study population was ≥ 25 kg/m2 (i.e., participants with overweight or obesity) or were at high-risk for diet-related chronic disease. Socioeconomic position of participants was reported most commonly from educational attainment level of participants, which was relatively high (e.g., >50% of participants had ~ 12 years or more) in 9 articles but widely varied in other articles. Race and/or ethnic information about participants was reported in 8 of 17 articles as follows:

- “16.2% Black; Brown, 28.1%; 52.2% White; 2.6% Asian, 1% Indigenous”^33^
- “14% Black, 27% Brown, 55% White, 3% Asian, 1% Indigenous"^34^
- “6% “Black”, 31% “Brown”, 62% “White”, 1% “Yellow/Oriental”^44^
- “White, Spanish”^37^
- “White British”^39^
- 100% Caucasian^32^
- “Brazilian”^45^
- “Korean”^46^

Studies examined dietary patterns consumed by participants ranging in age between 18 up to 75 years. Mean follow-up duration varied widely across studies, with a range from 6 months to approximately 15 years.

#### Intervention/exposure and comparator

Dietary intake assessment methods included food-frequency questionnaire,^32,33–37,40–42,44,46^ and 24-hour recalls.^31,38,39,43,45^ Dietary pattern methods included reduced rank regression,^39^ factor/cluster analysis^32^ and a priori score derivation in the remaining studies that used the Nova^*^ classification to define UPF intake. In the one article from an RCT,^32^ dietary pattern changes were examined by factor analysis 6 months after participants followed the investigator-assigned “Atlantic” diet, which was intended to reflect traditional patterns in northwestern Spain and Portugal (composed of home-cooked, local, fresh, and minimally processed foods).

* Details about the Nova food classification system can be found in this publication: Monteiro CA, Cannon G, Levy RB, . Ultra-processed foods: what they are and how to identify them. Public Health Nutr. 2019;22(5):936–941. doi:10.1017/S1368980018003762 30744710

Intake of UPF was analyzed as a continuous exposure variable (e.g., per 10% or 15% different in energy from UPF,^31,33,36,37,41,43^ per standard deviation,^35^ or by weight;^34,38,44,46^) and/or categorically (e.g., 700 vs. 234 g/d, g/day, servings/day, and/or quantiles).^31,33,35–38,40–46^ All included studies described the types of UPF contributing to the dietary pattern, but the number and types of UPF items and/or sub-groups within dietary patterns varied (e.g., 14 total items; 6 main sources; 3 sub-groups with 23 total items).

#### Outcomes

Included articles reported standardized procedures to measure body size and/or composition measurements in-person or used self-reported measures of weight and height. The following outcomes were reported across the body of evidence:

- Risk of overweight and/or obesity^40,46^
- BMI^31,36,43–46^
- Body composition (such as fat mass, fat mass index, % body fat)^37,39,43,44^
- Waist circumference^33,34,36,38,39,43^
- Weight^33,35,36^

### Synthesis of the evidence

This evidence synthesis focuses on the studies with fewer limitations, which included 1) studies that were designed to directly examine dietary patterns that vary in UPF, 2) studies that used 24-hour recall to collect dietary intake of UPF, and 3) studies that used a food processing classification system to categorize items as UPF. Across evidence, the direction of reported effect estimates were similar, regardless of statistical significance, and suggested that dietary patterns with higher compared to lower amounts of foods classified as UPF were significantly associated with higher risks of developing overweight and/or obesity, larger waist circumference, greater adiposity (e.g., fat mass, fat mass index, % body fat), and/or higher BMI.^31–38,40,41,43–46^ In 2 of these 14 articles, dietary patterns with few or no foods classified as UPF were significantly associated with lower risks of developing obesity and/or less BMI gain.^45,46^

The mean amount of UPF within dietary patterns ranged from ~5% up to 74% of total energy consumed in the populations for studies reporting this information. Common sources or types of UPF contributing to the dietary patterns included:

- sources of added sugar, primarily from refined grains and/or sugar-sweetened foods (e.g., mass-produced/packaged cookies, breads, buns, rolls, cakes, pastry)^31,33–46^
- processed meats and meat products (e.g., ham, sausage, hot dog, nuggets)^31–38,40–42,44–46^
- sugar-sweetened beverages (e.g., soft drinks, sports drinks, fruit drinks)^31–38,40–42,44–46^
- packaged (salty or savory) snack foods (e.g., chips, crackers),^31–34,36–38,41–45^
- pre-prepared, “fast”, ready-to-eat meals and dishes (e.g., pizza, instant noodles)^32–39,41–46^

Two of 16 articles reported a consistent direction of findings, but did not observe statistically significant associations between dietary patterns with varying amounts of UPF and risk of obesity and/or BMI.^39,42^ One of these articles used Nova 4 to classify UPF intake, and the other used reduced rank regression to examine a dietary pattern of foods typically classified as UPF (e.g., confectionary; buns, cakes, and pastries; sugar-sweetened soft drinks, processed meats). Therefore, the lack of statistical significance may be explained by these methodological inconsistencies.

### Conclusion statement and grade

The 2025 Dietary Guidelines Advisory Committee developed a conclusion statement to answer the question based on their review of evidence that examined dietary patterns with foods classified as UPF consumed by adults and older adults in relation to outcomes including risk of obesity, overweight, and/or adiposity (fat mass, waist circumference, BMI) (Table 11).

Table 11 Conclusion statement, grades for dietary patterns with varying amounts of ultra-processed food consumed by adults and older adults and body composition, and risk of obesity

Conclusion Statement | Dietary patterns consumed by adults and older adults with higher amounts of foods classified as ultra-processed food are associated with greater adiposity (fat mass, waist circumference, BMI) and risk of obesity and/or overweight. This conclusion statement is based on evidence graded as limited. (Grade: Limited)
Grade | Limited
Body of Evidence | 16 articles: 1 RCT, 15 articles from prospective cohort studies
Consistency | The body of evidence was consistent in magnitude and direction of effect estimates
Precision | Few concerns with narrow variance around effect estimates
Risk of bias | Serious concerns due to potential confounding, exposure misclassification, and not accounting for missing data
Directness | Some concerns that not all dietary patterns compared were directly varying in UPF
Generalizability | Participant characteristics, dietary patterns, and outcomes likely generalize but there were serious concerns with applicability of UPF to the U.S. population given the inconsistencies in amounts and types of UPF available in the countries and time periods included in the studies.

#### Assessment of Evidence

As described below, the body of evidence was assessed for the following elements used when grading the strength of evidence. This body of evidence includes both large and small studies, including studies with smaller sample sizes and null findings, which makes publication bias less likely.

##### Consistency

Direction and magnitude of effects were consistent in ~ 88% (16) of the studies: dietary patterns with higher compared to lower UPF were significantly associated with higher risk of overweight, greater BMI, waist circumference, and/or fat mass. Two studies also analyzed dietary patterns that were definitively low in UPF and observed they were related to a lower risk of obesity/overweight, and/or less gain in BMI or weight. For the 2 studies that did not report statistically significant findings, the direction of the relationship was similar to the other studies, supporting a positive association between dietary patterns with varying amounts of UPF and these health outcomes.

##### Precision

The studies were generally well-powered to address the research question and demonstrated effects from a wide range of sample sizes (n=661 to 348,748).

##### Risk of bias (Table 7 and Table 8)

Across domains, various risks of bias were identified. Most of the key confounders were accounted for across studies with few exceptions: race and/or ethnicity of participants was not reported or accounted for in 8 articles and anthropometry at baseline in 3 articles. Nine of the studies assessed diet only once (at baseline), and therefore do not fully account for potential change in dietary patterns that may have occurred over time. Assessment of foods and beverages as UPF based on dietary intakes collected via food-frequency questionnaires contributes to potential for exposure misclassification. Most studies objectively measured outcomes, but 6 used self-reported weight/height.

##### Directness

Studies were directly addressing the relationship of interest by examining dietary patterns with varying amounts of UPF, which were based on the Nova classification system in most studies. A few studies examined dietary patterns comprised of foods that are typically classified as “UPF” or likely consumed in ultra-processed versions but were not explicitly designated or cited as such with a specific classification system.

##### Generalizability

No studies were conducted in the U.S. Nine articles included a majority or all participants with overweight/obesity and/or high-risk for diet-related chronic disease. Nine studies did not report information on the racial or ethnic background of participants. Education was the most common information provided on SEP of participants and varied across studies. Most of the dietary patterns compared are generalizable to the U.S. population. However, a few sources of UPF (from select studies) may not be as generalizable (e.g., ‘acarajé’ or ‘instant pork mince dumpling’). The outcomes examined are generalizable to the U.S. population.

Table 12 Studies examining the relationship between dietary patterns with varying amounts of ultra-processed food consumed in adults and older adults and growth, body composition and composition and risk of obesity^a^

Article Information | Intervention/exposure and comparator | Results | Methodological considerations
Beslay, 2020^31^; France; NutriNet-Sante; Analytic N=110,260; 71871 Obesity; 55037 Overweight; Participant Characteristic:; - Health status: Mean BMI: 23.8; - Race and/or ethnicity: NR; - SEP info: Education (baseline): < high shcool: 18%; <2 y post-highschool: 17%; ≥2 y posthigh-school: 65%; Selection data: Excluded those with overweight or obesity at baseline, missing/extreme data, <2 dietary records and anthrompometric questionnaires, or < 6 months follow-up | Age at dietary pattern: 18 to 73.3 years (mean 43.1 [14.6]); UPF (Nova food classification system, group 4 [Monteiro, 2019]) 8 sub-groups: Fruits and Vegetables (UPF, reconstituted); Starchy foods and breakfast cereals (Industrial/flavored with additives); Meat, fish and egg (Processed/Industrial with additives); Dairy products (flavored or artificially sweetened; with additives); Beverages (sugary drinks, energy drinks, artificially sweetened); Sugary products (industrial cookies, cakes, candies with additives); Fats and sauces (dressing, mayonnaise, ketchup, other with additives); Salty snacks (chips, crisps, crackers with additives e.g., oil, salt, maltodextrin, flavors).; Method: Index/Score Analysis | Follow-up duration (F/U): 5 years, median; UPF & Risk of Overweight (model 3); - per 10%, HR: 1.10, 95% CI: 1.08, 1.13, p<0.001; - Q2, HR: 1.06, 95% CI: 0.99, 1.13; - Q3, HR: 1.18, 95% CI: 1.10, 1.26; - Q4, HR: 1.24, 95% CI: 1.16, 1.33; p-trend<0.001; UPF & Risk of Obesity (model 3); - per 10%, HR: 1.10, 95% CI: 1.06, 1.14, p<0.001; - Q2, HR: 1.05, 95% CI: 0.95, 1.17; - Q3, HR: 1.11, 95% CI: 1.00, 1.23; - Q4, HR: 1.16, 95% CI: 1.05, 1.30; p-trend=0.003; UPF & BMI ∆ (model 2); - per 10%, β 0.02, 95% CI: 0.01 to 0.02, p<0.001; - Q2, β 0.01, 95% CI: 0.004 to 0.02; - Q3, β 0.01, 95% CI: 0.01 to 0.02; - Q4, β 0.04, 95% CI: 0.04 to 0.05; p-trend<0.001 | - Did not account for: Race/Ethnicity; - Self-reported Weight, Height; Diet assessed once with 24 hour recall at baseline only; Funding: Ministère de la Sante´, Sante´ Publique France, Institut National de la Sante´ et de la Recherche Me´dicale, Institut National de la Recherche Agronomique, Conservatoire National des Arts et Me´tiers, and Universite´ Sorbonne Paris Nord
Calvo-Malvar, 2021 A^32^; Spain; Galiat study; Analytic N=661; Participant Characteristic:; - Health status: CVD, 16-18%; DM, 6%; - Race and/or ethnicity: 100% Caucasian; - SEP: Employed ~48-52%; Retired ~14-20%; Other ~32-34%; Education: None, ~10%; Elementary, 36-42%; Secondary 32-36%; Uni+ 16-18%; Selection data: Excluded those with alcoholism, pregnancy, major CVD, dementia, predicted survival <1 y; on lipid-lowering medication. Analyses include intention-to-treat (ITT) with imputed data for missing values, and per-protocol (PP) including only those with complete data | Dietary patterns at age(s):~ 3 to 85 years; “[underlined: Caloric”] dietary pattern: Positive: high-energy drinks, processed meats, precooked food, pizza, salty snacks, mayonnaise and ketchup, sweets. Negative: wine; Method: RCT: Factor/Cluster | F/U: 6 months; ‘Caloric’ dietary pattern and; - ∆ Weight (ITT), β: 0.146, −0.030, 0.332; p-trend=0.103; - ∆ Weight (PP), β: 0.172, 95% CI: 0.002, 0.343; p-trend=0.047 | - Did not account for: Race/Ethnicity; - Included a random representative sample drawn from Spanish National health System Register (ages 18-85) and relatives who shared a home (ages 3-85) in family unit ≥ 2 members; Funding: ERDF-Innterconecta for Galicia Program
Canhada, 2019^33^; Brazil; ELSA-Brasil; Analytic N=11827 (Wt; WC); 4525 OW/Ob; 4771 Ob; Participant Characteristic:; - Health status: Excluded those with chronic diseases at baseline; Mean BMI, 26.8, WC, cm, 90.6; - Race and/or ethnicity: Black, 16.2%; Brown, 28.1%; White, 52.2%; Asian, 2.6%; Indigenous, 1%; - SEP info: Median family income, 5x Brazilian minimum wage; Education: < elementary, 5%; Elementray, 6%; Secondary, 35%; College/University, 54%; Selection data: All Civil servants of Brazilian public academic institutions; Excluded those with no FFQ data, missing data on weight, WC or covariates, and implausible intake, chronic disease, on meds influencing consumption; LFU, or had bariatric surgery between visits. | Age at dietary pattern: 35 to 75 years, mean 51 years at baseline; UPF (Nova food classification system, group 4 [Monteiro, 2019]) 13 sub-groups: Bread; Sweets, candies; Sweetened sodas/juices; Salty pastries, chips; Cakes; Processed meat; Pasta and pizzas; Cookies, crackers; Mayonnaise, margarine, cream cheese; Yogurt with additives; Cereal bars; Distilled alcoholic beverages; Soup; Method: Index/Score Analysis | F/U: 3.8 years, mean; UPF & Risk of Overweight/Obesity, n=4527; - Q2, RR: 1.14, 95% CI: 0.98,1.33; - Q3, RR: 1.36, 95% CI: 1.18,1.57; - Q4, RR: 1.2, 95% CI: 1.03,1.4; UPF & Risk of Obesity, n=4771; - per 15%, 1.06, 95% CI: 0.96,1.17; - Q2, RR: 1.12, 95% CI: 0.95,1.32; - Q3, RR: 1.01, 95% CI: 0.85,1.21; - Q4, RR: 1.02, 95% CI: 0.85,1.21; UPF & WC, incident large gain; - per-15%, 1.15, 95% CI: 1.06,1.25; - Q2, RR: 1.11, 95% CI: 0.94,1.33; - Q3, RR: 1.23, 95% CI: 1.04,1.46; - Q4, RR: 1.33, 95% CI: 1.12,1.58; UPF & Weight, incident large gain; - per-15%, 1.12, 95% CI: 1.03,1.22; - Q2, RR: 1.15, 95% CI: 0.97,1.37; - Q3, RR: 1.2, 95% CI: 1.02,1.42; - Q4, RR: 1.27, 95% CI: 1.07,1.5; *Stronger association observed in non-Whites than other race/skin colour groups | - Did not account for: TEI; - Diet assessed once at baseline only with validated FFQ; FFQ was not designed for UPF via NOVA classification; additional analyses: adjusted further for TEI, Fruit and Vegetable intake, excluding sweetened beverages; and tested interactions between sex, race/color, and age; Funding: Brazilian Ministry of Health (Department of Science and Technology) and Ministry of Science, Technology and Innovation; National Council for Scientific and Technological Development
Canhada, 2023^34^; Brazil; ELSA-Brasil; Analytic N=8065; Participant Characteristic:; - Health status: 62% never smokers; - Race and/or ethnicity: “14% Black, 27% Brown, 55% White, 3% Asian, 1% Indigenous”; - SEP info: Education: 59% college degree; Income: 747-2352 Brazilian reais (P25-P75); Selection data: Excluded those w MetS at baseline, LFU, missing/implausible diet or anthropometric data; Included active or retired employees of research/education institutions who were not pregnant | Age at dietary pattern: 49 years, median; UPF (Nova food classification system, group 4 [Monteiro, 2019]) e.g., packaged products such as bread (light, toasted, sweet, whole grain), cheese bread, simple cake, stuffed cake, salty biscuit, sweet biscuit with filling, sweet biscuit without filling, light mayonnaise, mayonnaise, light sweetened yogurt, sweetened yogurt, light cream cheese, cream cheese, margarine/vegetable cream, sausage, hamburger (steak), sliced turkey breast, ham/mortadella/ salami, readypackaged pizza, instant noodles, baked snacks, fried snacks, afro-Brazilian bean fritter (acarajé), hot dogs, instant soup, creamy ice cream, fruit popsicle, caramel/candy, gelatin, chocolate powder, chocolate bar, pudding, fruit jam/jelly, cereal bar, diet soda, soda, industrialized juice with sugar, industrialized juice without sugar, industrialized juice with sweetener, artificial juice with sugar, artificial juice without sugar, artificial juice with sweetener, distilled alcoholic beverages; Method: Index/Score Analysis | Results at F/U:~ 2 and 8 years; UPF 700 vs. 234 g/d & WC: 0.7cm, p=0.003 | - Did not account for: N/A (all accounted for); - Diet assessed once via FFQ at baseline; Misclassification possible due to UPF intake based on FFQ; Outcomes objectively measured; Indirect outcome of Metabolic Syndrome; Funding: Brazilian Ministry of Health (Department of Science and Technology) and Ministry of Science, Technology, and Innovation; National Council for Scientific and Technological Development
Cordova, 2021^35^; Denmark, France, Germany, Greece, Italy, the Netherlands, Norway, Spain, Sweden, and the United Kingdom; EPIC; Analytic N=348748; Participant Characteristic:; - Health status: BMI <25 48-59%; Overweight 31-38%; Obesity 10-14%;; - Previous illness, T2D, CVD, cancer: 7-8%; - Race and/or ethnicity: NR; - SEP info: University degree: Q1, 23%; Q2, 24%; Q3, 26%; Q4, 37%; Q5, 25%; Selection data: Excluded those who were pregnant at baseline, or missing data on diet, lifestyle, or follow-up, reported extreme energy intake or unreliable anthropometric data | Age at dietary pattern: 25 to 70 years; UPF (Nova food classification system, group 4 [Monteiro, 2019]) w/o alcoholic drinks: e.g., Vegetables and legumes in ultra-processed medium; Potato products; Breads (UPF); Pastries, buns, and cakes; Biscuits; Breakfast cereals; Pizza and focaccia (dough); Pasta (filled); Processed meat (beef, pork and fish); Meat alternatives; Dairy substitute products; Processed cheese; Dairy desserts and drinks (UPF version); Ice cream, ice pops and frozen yogurts; Industrial desserts; Fruit drinks, iced tea and other sweetened beverages; Beverages dry weight; Artificial sweeteners; Sweet snacks; Soft drinks; Packaged salty snacks; Instant and canned soups; ; Margarine; Vegetable spread and products; Alcohol-free versions of alcoholic beverages; Other: Ready meals; Nutrition powders and drinks; Sauces, dressing and gravies; Nova 4 Q5 v. Q1 had similar Mediterranean diet scores but higher (not statistically) in intakes from: Dairy; Sugar/confectionary; Cakes/biscuits; Soft drinks; Lower in: Fruit; Legumes; Meat/meat products; Fish; Cereals; Alcoholic drinks; Similar Vegetables; Egg; Potatoes; Added Fat; Coffee; Method: Index/Score Analysis | F/U: 5 years, median; UPF & Weight gain; - per SD, β: 0.118, 95% CI: 0.085, 0.151; - Q1, β: 1, ref; - Q2, β: −0.009, 95% CI: −0.095, 0.076; - Q3, β: 0.101, 95% CI: −0.002, 0.205; - Q4, β: 0.193, 95% CI: 0.105, 0.282; - Q5, β: 0.352, 95% CI: 0.262, 0.442; - p-trend<0.001 | - Did not account for: Race/Ethnicity; - Diet assessed once with FFQs, validated but differed between cohort waves; Outcomes at baseline were measured in some countries and self-reported in others;; - Residual method was used for energy adjustment; Conducted repeat analyses substituting NOVA 1 for NOVA 4; Conducted a range of sensitivity tests (Soft drinks as driver; by Sex, by Age, by BMI); Funding: Fondation de France^*^; * Cordova, 2021 additional funding: National cohorts supported by individual funders: Ligue Contre le Cancer, Institut Gustave-Roussy, Mutuelle Générale de l’Education Nationale, Institut National de la Santé et de la Recherche Médicale (INSERM) (France); German Cancer Aid, German Cancer Research Center (DKFZ), Federal Ministry of Education and Research (BMBF) (Germany); Associazione Italiana per la Ricerca sul Cancro-AIRC-Italy and National Research Council (Italy); Dutch Ministry of Public Health, Welfare and Sports (VWS), Netherlands Cancer Registry (NKR), LK Research Funds, Dutch Prevention Funds, Dutch ZON (Zorg Onderzoek Nederland), World Cancer Research Fund (WCRF), Statistics Netherlands (The Netherlands); Health Research Fund (FIS-ISCIII), the Regional Governments of Andalucía, Asturias, Basque Country, Murcia, Navarra, and the Catalan Institute of Oncology (Barceloan), Spain); Cancer Research UK and Medical Research Council (EPIC-Norfolk; EPIC-Oxford)
González-Palacios, 2023^36^; Spain; PREDIMED (Subset); Analytic N=5373; Participant Characteristic:; - Health status: 100% highcardiometabolic risk; 100% Overweight or Obesity; 30% T2D; 45% never smokers; - Race and/or ethnicity: NR; - SEP info: Education: 21% College; 29% secondary; Employment: 19% current; 58% retired; 77% maried; Selection data: All participants were at highCMR (3+ criteria for Metabolic Syndrome) | Dietary patterns at age(s): 55 to 75 years; [underlined: UPF] (Nova food classification system, group 4 [Monteiro, 2019]) 6 sub-groups:; 1) Dairy products (Flavored milk drinks; Petit-suise; cheese portions or cream cheese; custard, pudding or similar and Ice cream);; 2) Processed meats (Ham; Processed meats such as dried sausage, chorizo or similar; patés and foie gras; burgers and meatballs);; 3) Sweets (Plain, whole grain and chocolate biscuits; croissants, pastries or similar; doughnuts; muffins; Spanish churros or similar; pies; chocolates and chocolate; cocoa powder; Spanish nougat; marzipan or similar);; 4) Fast-foods (Crisps; pizza, croquettes, packet or canned soups, margarine, commercial mayonnaise, mustard, ketchup, packed fried tomato sauce, savory packed snacks);; 5) Beverages (Soft drinks (sugar- and artificially-sweetened) and commercial fruit juices);; 6) Alcoholic Beverages (Liquors and spirits (whisky vodka, gin and cognac); All Nova 4 items from FFQ: Flavored milk drinks; Petit-suise; Cheese portions or cream cheese; Custard, pudding or similar; Ice cream; Ham; Processed meats such as dried sausage, chorizo or similar; Patés and foie gras; Burgers and, meatballs; Crisps; Breakfast cereals; Pizza; Margarine; Plain biscuits; Whole grain biscuits; Chocolate biscuits; Croissants, pastries or similar; Doughnuts; Muffins; Spanish churros or similar; Pies; Chocolates and chocolate; Cocoa powder; Spanish nougat; Marzipan or similar; Croquetas, fishcakes, pasties, or similar; Packet or canned soups; Mustard; Commercial mayonnaise; Fried tomato sauce or ketchup; Snacks other than crisps; sugar-sweetened soft drinks; artificially-sweetened soft drinks; commercial fruit juices; Liquors; Spirits: whisky, vodka, gin and cognac.; Method: Index/Score Analysis | F/U: 6-12 months; [underlined: UPF, g/d (Q1, ref)]; BMI, kg/m2; - Q2, β: 0.18, 95% CI: 0.12; 0.23; - Q3, β: 0.30, 95% CI: 0.24; 0.36; - Q4, β: 0.39, 95% CI: 0.33; 0.46; p <0.0001; - per 100g, β: 0.08, 95% CI: 0.06; 0.09; p <0.0001; WC, cm; - Q2, β: 0.41, 95% CI: 0.22; 0.59; - Q3, β: 0.78, 95% CI: 0.58; 0.99; - Q4, β: 1.03, 95% CI: 0.81; 1.26; p<0.0001; - per 100g, β: 0.18, 95% CI: 0.11; 0.24; p <0.0001; Weight, kg; - Q2, β: 0.50, 95% CI: 0.36; 0.63; - Q3, β: 0.83, 95% CI: 0.67; 0.98; - Q4, β: 1.09, 95% CI: 0.91; 1.26; p <0.0001; - per 100g, β: 0.21, 95% CI: 0.17; 0.26; p <0.0001; [underlined: UPF, % TEI (Q1, ref)]; BMI, kg/m2; - Q2, β: 0.16, 95% CI: 0.11; 0.21; - Q3, β: 0.27, 95% CI: 0.21; 0.33; - Q4, β: 0.40, 95% CI: 0.33; 0.46; p <0.0001; - per 10%, β: 0.18, 95% CI: 0.13; 0.22; p <0.0001; WC, cm; - Q2, β: 0.32, 95% CI: 0.14; 0.51; - Q3, β: 0.68, 95% CI: 0.48; 0.89; - Q4, β: 0.96, 95% CI: 0.73; 1.18; p<0.0001; - per 10%, β: 0.44, 95% CI: 0.29; 0.59; p <0.0001; Weight, kg; - Q2, β: 0.46, 95% CI: 0.32; 0.59; - Q3, β: 0.73, 95% CI: 0.58; 0.88; - Q4, β: 1.06, 95% CI: 0.89; 1.23; p <0.0001; - per 10%, β: 0.48, 95% CI: 0.36; 0.60; p <0.0001 | - Did not account for: Race/Ethnicity (Spanish), Anthropometry at baseline (100% Overweight/Obesity but Q4 UPF had higher baseline weight/WC/BMI); - Diet assessed with FFQ at baseline, 6 and 12 months; Misclassification possible due to UPF intake based on FFQ; All participants reduced UPF consumption of 6 sub-groups from baseline to 6 months and to 12 months (cointervention effects possible); Outcomes objectively measured; Funding: Spanish Institutions for funding scientific biomedical research, CIBER Fisiopatología de la Obesidad y Nutricion ´ and Instituto de Salud Carlos III via Fondo de Investigacion ´ para la Salud; Especial Action Project entitled: Implementacion ´ y evaluacion ´ de una intervencion ´ intensiva sobre la actividad física Cohorte; European Research Council; Recercaixa; Generalitat Valenciana; Ministerio de Ciencia e Investigacion
Konieczna, 2021^37^; Spain; PREDIMED Plus; Analytic N=1485; Participant Characteristic:; - Health status: 100% with Metabolic Syndrome, 3+ criteria: 75% Obesity; 93% abdominal Obesity; 22% T2D; 26% Depression; - mean BMI, 32.5; WC, 107.3cm; LM 56.%; FM 40.4%; Visceral fat, 2305g; - Race and/or ethnicity: White, Spanish, data NR; - SEP info: Higher education, 21.6%; Selection data: All had ≥ 3 criteria for Metabolic Syndrome and BMI 27-40 kg/m2, free of CVD at baseline, included subsample who underwent DXA scans; Excluded those with missing/extreme diet data; missing visceral fat and FFQ at baseline, missing sedentary behavior at baseline | Dietary patterns at age(s): 55 to 75 years at baseline; [underlined: UPF] (Nova food classification system, group 4 [Monteiro, 2019]) 7 sub-groups: Dairy products; Processed meat; Pre-prepared dishes; Snacks and fast-foods; Sweets; Nonalcoholic beverages; Alcoholic beverages; Method: Index/Score Analysis | Results at F/U:1 year; UPF & Fat mass; - per-10%, β: 0.09, 95% CI: 0.06, 0.13; p<0.0001; - T2, β: 0.09, 95% CI: 0.05, 0.13; - T3, β: 0.15, 95% CI: 0.11, 0.19; p<0.0001; UPF & Visceral fat; - per-10%, β: 0.09, 95% CI: 0.05, 0.13; p<0.0001; - T2, β: 0.05, 95% CI: 0.00, 0.10; - T3, β: 0.13, 95% CI: 0.07, 0.19; p<0.0001; UPF & Android-to-gynoid fat ratio; - per-10%, β: 0.05, 95% CI: 0.00, 0.09; p=0.031; - T2, β: 0.05, 95% CI: 0.00, 0.10; - T3, β: 0.11, 95% CI: 0.05, 0.16; p=0.003 | - Did not account for: Race/Ethnicity (100% Spanish); - Diet assessed via FFQ at baseline, 3 months, 12 months with validated FFQ; Sensitivity analyses: diet quality factors, adherence to ER-MedDiet; mediation analyses: extent to which nutritional variables and overall adiposity parameters might be responsible for the association between concurrent changes in UPF consumption and regional fat deposition; modification by age, T2D prevalence, smoking status, sedentary behavior, Obesity; Abdominal obesity; Funding: European Research Council
Li, 2021^38^; China; China Nutrition and Health Survey; Analytic N=12451; Participant Characteristic: by NOVA 4 g/d; - Health status: mean BMI: 22.7 to 23.2; p<0.001;; Mean WC: 78.9 to 80.9, p<0.001;; Overweight/Obesity: 21.7% to 26.9%;; p<0.001; Central Obesity; 24.9% to 28.2%;; p=0.070; DM: 9.2%; - Race and/or ethnicity: NR (100% Chinese); - SEP: Income: Low, ~ 20 to 32%; Medium, 32 to 34%; High, 35 to 49%; p<0.001; Selection data: Enrolled those with at least two surveys 1997-2011; plausible energy intake, and diet and anthropometric data | Age at dietary pattern: mean 43.7 years; UPF (Nova food classification system, group 4 [Monteiro, 2019]) 10 main sources (~51% all UPF): Instant pork-mince steam bun; Bread; Instant noodle; Cookies; Cake; Instant pork-mince dumpling; Sausage; Liquor; Soybean paste; Packaged snacks; Method: Index/Score Analysis | F/U: 12 years total, NR; UPF & Risk of Overweight/Obesity,; 0g/d, HR: 1, ref; - 1-19 g/d, HR: 1.45, 95% CI: 1.26, 1.65; - 20-49 g/d, HR: 1.34, 95% CI: 1.15, 1.57; - ≥50 g/d, HR: 1.45, 95% CI: 1.21, 1.74; - p<0.001; UPF & WC,; 0g/d, HR: 1, ref; - 1-19 g/d, HR: 1.54, 95% CI: 1.38, 1.72; - 20-49 g/d, HR: 1.35, 95% CI: 1.19, 1.54; - ≥50 g/d, HR: 1.50, 95% CI: 1.29, 1.74; - p<0.001 | - Did not account for: Anthropometry; - Diet assessed with repeat (3) 24 hour recalls; Foodprocessing status discussed and based on consensus e.g., ‘fruit or milk drinks’ were UPF if containing sweeteners, preservatives, or other additives’; - Other factors associated with weight status were age, education, urbanization (strongest), smoking, and physical activity, but not statistically significant; Funding: None
Livingstone, 2022 DP^39^; United Kingdom; BIOBANK; Analytic N=11735; Participant Characteristic:; - Health status: Mean BMI, 24.6; WC, cm, 83; BF%, 27.1; - Race and/or ethnicity: 100% White British; - SEP info:; ○ Education: College or university degree, 54.6%; A/AS levels , 13.3%; O levels/GCSE/CSEs, 19.8%; Professional qualifications, 8.5%; None/prefer not to answer, 3.8%; ○ Townsend Deprivation Index: Least 24%, 2nd least 24%, Mid 20%, 2nd Most 18%, Most 14%; Selection data: Excluded those with missing exposure/outcome/covariate/ >10% genetic data, <2 diet assessments; pregnancy; non-White-British ancestry; heterozygous outliers; or second cousins of pairs. | Dietary patterns at age(s):40 to 69 years; [underlined: “DP1]”: higher intake of buns, cakes and pastries, confectionary and sweet biscuits; sugar-sweetened soft drinks; high-fat cheese; butter; processed meats; negatively associated with consumption of fruits, vegetables, low-fat yoghurt; Method: RRR: Response variables were discretionary foods and beverages [%E]; SFA [%E]; fiber density [g/MJ] | Results at F/U:6.3 years, mean; DP1 and:; - Risk of Obesity, HR: 1.09, 95% CI: 0.99,1.19; - Risk of High-% body fat, HR: 1.03, 95% CI: 0.98,1.08; - Risk of High-WC, HR: 1.08, 95% CI: 1.03,1.14 | - Did not account for: N/A (all controlled for); - Diet assessed at five times with 24-h recalls and “usual baseline” DP based on average from ≥ 2; Funding: Select authors funded by National Health and Medical Research Council Emerging Leadership Fellowship; Lister Prize Fellowship
Mendonca, 2016^40^; Spain; SUN Cohort; Analytic N=8,451; Participant Characteristic:; - Health status: BMI: ~22 kg/m2; Weight: ~62-63 kg; Smoking status: ~2024% current smoker, ~25-26% former smoker; PA: ~22-23 MET-h/wk; TV time: ~1.5-1.6 h/d; Q4 v. Q1 UPF had highest BMI, more likely current smokers, and more TV time; - Race and/or ethnicity: NR; - SEP info: Education: ~7779% graduated university, ~16-19% master or doctoral; Marital status: ~45-48% single, ~46-50% married; Selection data: Excluded those with overweight or obese at baseline; total energy intake values outside of predefined limit; pregnancy at baseline or during follow-up; previously diagnosis of chronic disease at baseline (e.g.DM, Cx, CVD); weight change >10 kg in the 5 y preceding entry into the study; lost to follow-up, missing values in ≥1 variable of interest | Dietary patterns at age(s):37.6 [11.0] years; [underlined: UPF] (Nova food classification system, group ref) 4 [Monteiro, 2019]) 8 main sources: Processed meat (ham, sausage, chorizo, salami, mortadella, hamburger); Cookies; Pastries (muffins, doughnuts, croissants and confectionary); Breakfast cereals; SSBs; Fruit drinks in bottles; Margarine; Chocolate; Method: Index/Score Analysis | Results at F/U:8.9 years median; UPF & Risk of Overweight/Obesity (Q1: HR 1, ref); - Q2: HR 1.15, 95%CI: 1.01, 1.32; - Q3: HR 1.24, 95%CI: 1.09, 1.43; - Q4: HR 1.26, 95%CI: 1.10, 1.45 | - Did not account for: Alcohol (Differed at baseline but not adjusted; unclear if included); Race/ethnicity (all Spanish); - Diet assessed once via FFQ (validated) at baseline; FFQ was not designed for UPF; Funding: Carlos III Health Institute; European Regional Development Fund, regional government of Navarra, and University of Navarra
Mirmiran 2022^41^; Iran; Tehran Lipid/Glucose; Analytic N=1299; Participant Characteristic:; - Health status: 61% Overweight/Obesity; ~80% non-smokers; - Race and/or ethnicity: NR (Iranian); - SEP: Most 12 years + education; Selection data: Excluded those with unhealthy metabolic phenotype, younger than 19 years old, missing data/LFU/implausible dietary data | Age at dietary pattern: 29 to 49 years; [underlined: UPF](Nova food classification system, group 4 [Monteiro, 2019]) 9 sub-groups: Dairy products (ice cream, chocolate milk); Processed meat (sausages, burgers, hot dogs); Pizza; Cakes and biscuits; Candies and chocolates; Mayonnaise, margarine and hydrogenated oils; Soft drinks (carbonated soft drinks); Salty snacks (potato chips and pufak); Creamy cheese; Method: Index/Score Analysis | F/U: ~6 years; UPF & Risk of Metabolically Unhealthy-Normal Weight (MUNW) (Q1, ref); - Q2, HR: 0.85, 95% CI: 0.51, 1.40; - Q3, HR: 1.43, 95% CI: 0.85, 2.39; - Q4, HR: 1.83, 95% CI: 1.14, 2.92; - per 10%, HR: 1.54, 95% CI: 1.20, 1.98; p=0.001; UPF & Risk of Metabolically Unhealthy-Overweight (MUOW)(Q1, ref); - Q2, HR: 1.01, 95% CI: 0.77, 1.34; - Q3, HR: 1.11, 95% CI: 0.83, 1.48; - Q4, HR: 1.19, 95% CI: 0.90, 1.57; - per 10%, HR: 1.02, 95% CI: 1.01, 1.03; p=0.021; Sensitivity analyses of individual UPF support Processed meat and Salty snack sub-groups as significant drivers for both MUOW and MUNW | - Did not account for: Race/Ethnicity (Iranian, data NR), Physical activity (differed by UPF in MHOW), Alcohol (most were nonconsumers), Smoking (most non-smokers); - Diet assessed once via FFQ; Misclassification possible due to UPF intake based on FFQ; Outcomes objectivey measured; Indirect outcome of ‘metabolically unhealthy phenotype’ stratified by baseline status of normal weight and Overweight/Obesity; - Funding: Shahid Beheshti University Medical Sciences
Pant, 2023^42^; Australia; ALSWH; Analytic N=10006; Participant Characteristic:; Health status:; - BMI: Mean 26.8 (Q2 & Q3 higher BMI); Overweight, 32-34%; Obesity, 21-25%; - T2D, 3-6% Hypertension, 25-30%; Cancer, 3-4% ~25% post-menopause; Race and/or ethnicity: NR; SEP info:; - Education: 15-17% None, 29-33% primary school, 15-18% high school; 34% trade, 16-18% diploma, 9-10% university degree, 5-7% Master or PhD degree; - Income, $AU: 6-8% <16K; 50-52% 16K-51,999; 42-43% >51,999; Selection data: Women without CVD and with complete data (FFQ, plausible) | Age at dietary pattern: 52.5 y, mean (50 to 55y, third survey year 2001); [underlined: UPF] (Nova food classification system, group 4 [Monteiro, 2019]) Top 12 sources in rank order: Ready-made meals; Industrial packaged breads; Milk-based drinks; Breakfast cereals; Processed meats; Margarine and other spreads; Industrial potato chips; Processed cakes; Snacks; Ice cream; Biscuits; Confectionary; Method: Index/Score Analysis | F/U: 15 years ~ until 2016; UPF & Risk of Obesity; - Q2, OR: 1.07, 95% CI: 0.80, 1.43, p=0.67; - Q3, OR: 1.29, 95% CI: 0.97, 1.73, p=0.08; - Q4, OR: 1.05, 95% CI: 0.77, 1.43, p=0.76; - Q5, OR: 1.16, 95% CI: 0.85, 1.60, p=0.36; - p-trend=0.52 | - Did not account for: Race/Ethnicity,; - Diet assessed once via FFQ; Misclassification possible due to UPF intake based on FFQ; Outcome self-reported; Primary outcome was CVD; Funding: CAUL and its Member Institutions
Rauber, 2021^43^; United Kingdom; BIOBANK; Analytic N=22659; Participant Characteristic:; - Health status: BMI, mean: ~26.7 kg/m2; Obesity: ~19%; WC, mean: ~87.989.2 cm; Abdominal obesity: ~25%; mean % Body Fat: ~31% ; Physical activity: ~1518% low, ~36-37% moderate, ~31-37% high, ~12-15% missing; - Race and/or ethnicity: NR; Participants from across England, Scotland, and Wales; - SEP info: all participants evenly distributed (~20% were in each deprivation index category); UPF Q4 v.Q1 were more likely to be in most deprived; Selection data: Excluded those with obesity or high WC at baseline, implausible food intake, pregnant at baseline, invalid BMI, WC, or body fat data | Dietary patterns at age(s):40 to 69 y at baselineInclude; [underlined: UPF] (Nova food classification system, group 4 [Monteiro, 2019]) 6 main sources: Snacks, desserts (33%, confectionary, pastries, packaged salty snacks); Breads (21%, bagel, buns, rolls); Ready-to-heat meals (16% frozen or shelf-stable); Beverages (15%, milk-based, soft and fruit drinks, fruit juices, alcoholic, coffee); Spreads, sauces, other (9% e.g., margarine, gravies); Cereals breakfast (6% sweetened oat/cornflake cereals); Method: Index/Score Analysis | F/U: 5.6 y for Ob or high WC, 5.8 y for ≥ 5% BMI or WC increases, 1.8 y for ≥ 5% BF increase; UPF & Risk of Obesity; - Q2 , HR: 1.50, 95% CI: 0.87, 2.58; - Q3 , HR: 1.03, 95% CI: 0.58, 1.83; - Q4 , HR: 1.79, 95% CI: 1.06, 3.03; p=0.068; - per 10%, HR: 1.10, 95% CI: 0.99, 1.22; UPF & ≥ 5% Body Fat increase; - Q2 , HR: 1.05, 95% CI: 0.96, 1.16; - Q3 , HR: 1.05, 95% CI: 0.95, 1.16; - Q4 , HR: 1.14, 95% CI: 1.03, 1.25; p<0.001; - per 10%, HR: 1.03, 95% CI: 1.01, 1.05; UPF & ≥ 5% BMI increase; - Q2 , HR: 1.07, 95% CI: 0.98, 1.18; - Q3 , HR: 1.07, 95% CI: 0.97, 1.17; - Q4 , HR: 1.31, 95% CI: 1.20, 1.43; p<0.001; UPF & high WC; - Q2 , HR: 1.17, 95% CI: 1.03, 1.34; - Q3 , HR: 1.21, 95% CI: 1.06, 1.38; - Q4 , HR: 1.30, 95% CI: 1.14, 1.48; p<0.001; - per 10%, HR: 1.06, 95% CI: 1.03, 1.08; UPF & ≥ 5% WC increase; - Q2 , HR: 1.13, 95% CI: 1.05, 1.22; - Q3 , HR: 1.18, 95% CI: 1.10, 1.27; - Q4 , HR: 1.35, 95% CI: 1.25, 1.45; p=0.014; - per 10%, HR: 1.06, 95% CI: 1.05, 1.08 | - Did not account for: Race/Ethnicity; - Diet assessed with 24h recall; Funding: Fundação de Amparo à Pes quisa do Estado de São Paulo (FAPESP)
Rudakoff 2022^44^; Brazil; 1978/1979 Ribeirão Preto; Analytic N=1021 (LM n=815); Participant Characteristic:; - Health status: NR; - Race and/or ethnicity: 62% “White”, 6% “Black”, 31% “Brown”, 1% “Yellow/Oriental”; - SEP info: Income, Min. Wage (MW): <5, 34%; 5-9.9 31%; >9.9 27%; Selection data: Excluded those w Metabolic Syndrome at baseline, LFU, missing or implausible diet data; Birthcohort | Dietary patterns at age(s):23 to 25yInclude; [underlined: UPF] (Nova food classification system, group 4 [Monteiro, 2019]) 14 items: Sugarsweetened beverages; Savory snacks; Dairy products; Candies; Cold meats; Cake; UP Bread; Crackers; Instant noodles; Snacks; Mayonnaise; Granola; Margarine; Distilled drinks; Method: Index/Score Analysis | Results at F/U:~14y (age 37 to 39y); UPF % g and:; - BMI, β: 0.04, 95% CI: 0.00, 0.08; p= 0.058; - FMI, β: 0.04, 95% CI: 0.00, 0.07; p= 0.021; - Body fat, β: 0.09, 95% CI: 0.02, 0.16; p= 0.010; - Android FM, β: 0.01, 95% CI: 0.00, 0.02; p= 0.005; - Gynoid FM, β: 0.02, 95% CI: 0.00, 0.04; p= 0.017; - Android/Gynoid FM ratio, β: 0.0006, 95% CI: −0.0004, 0.002; p= 0.225; UPF % TEI and:; - BMI, β: 0.06, 95% CI: 0.00, 0.12; p= 0.038; - FMI, β: 0.06, 95% CI: 0.00, 0.10; p= 0.018; - Body fat %, β: 0.11, 95% CI: 0.02, 0.21; p= 0.017; - Android FM, β: 0.01, 95% CI: 0.00, 0.02; p= 0.071; - Gynoid FM, β: 0.02, 95% CI: 0.00, 0.04; p= 0.038; - Android/Gynoid FM ratio, β: 0.0004, 95% CI: −0.0001, 0.002; p= 0.556 | - Did not account for: Anthropometry (at baseline), Race/Ethnicity; - Diet assessed once via FFQ; Misclassification possible due to UPF intake based on FFQ; Outcomes objectively measured; Funding: Coordination for Improvement of Higher cation Personnel-Brazil, the National Council for Scientific and Technological Development -CNPq; Research Support Foundation of the State of São Paulo; Teaching, Research, and Assistance Support Foundation
Santos, 2023^45^; Brazil; NutriNet-Brasil; Analytic N=9551; Participant Characteristic:; - Health status: ~48% Overweight or Obesity; 76% never smoker; 58% Physically active; - Race and/or ethnicity: NR (Brazilian); - SEP info: Education: 88% 12 years+; 63% from Southeast and 18% from South regions (more economically developed); Selection data: Excluded those with pregnancy; implausible (< 2 months prebaseline, >6 months postF/U; outlier) or missing BMI or covariate data | Dietary patterns at age(s):18 years +; [underlined: UPF] (Nova food classification system, group 4 [Monteiro, 2019]) 3 sub-groups with 23 items comprising “UPF-score”: 1) UPF Snacks: packaged chips or crackers; cookies; cake snacks; cereal bars; ice cream or popsicle; chocolate bar or candies; and sugared breakfast cereals (7 items); 2) UPF Drinks: regular or diet soda; canned or bottled fruit juice (Del Valle®-type); powdered drink mix (Tang®-type); chocolate-flavoured drink (Nescau®-type); tea-based beverage (ice tea-type); and fruit- or chocolate-flavoured yogurt (6 items); 3) UPF Other: sausage, hamburger or nuggets; ham, salami or mortadella; loaf, hot dog, or hamburger bun; margarine; French fries (either frozen or from restaurant chains such as McDonald’s®); mayonnaise, ketchup or mustard; store-bought salad dressing; instant noodles (Miojo®-type) or packaged soup; pizza (either frozen or from restaurant chains, such as Pizza Hut® or Domino’s®); and frozen lasagna or other frozen readymade meals (10 items); Method: Index/Score Analysis | F/U: 13 months; UPF & BMI gain after 15 months,; - Q2, RR: 1.07, 95% CI: 0.92, 1.25; - Q3, RR: 1.18, 95% CI: 1.02, 1.38; - Q4, RR: 1.23, 95% CI: 1.06, 1.43; - Q5, RR: 1.34, 95% CI: 1.15, 1.56; - linear, p-trend<0.001; UPF & BMI gain after 15 months,; - Q2, RR: 0.91, 95% CI: 0.80, 1.04; - Q3, RR: 0.82, 95% CI: 0.72, 0.93; - Q4, RR: 0.84, 95% CI: 0.73, 0.98; - Q5, RR: 0.80, 95% CI: 0.69, 0.94; - linear, p-trend<0.01 | - Did not account for: Race/ethnicity (Brazilian); TEI; - Diet assessed once with 24-hour recalls (~ 3); Self-reported height and weight used for BMI; Mediation showed 26% of total effect on BMI gain due to Nova 4 score and 15% due to Nova 1 score; Funding: Brazilian Ministry of Health through CNPq, the Brazilian National Council for Scientific and Technological Development; FAPSEP; São Paulo state Research Foundation; UMANE
Tan 2023^46^; Korea; KOGES; Analytic N=17310; Participant Characteristic:; - Health status: mean BMI ~22; majority of women non-smokers (97-98%) and non-alcohol consumers; majority of men consumd alcohol (67-74%); - Race and/or ethnicity: NR (Korean); - SEP info: Education: Majority some or high; Selection data: Excluded those with metabolic diseases at baseline (e.g., CVD, DM); missing/implausible diet or GBCO data; Included 73% female participants and reported data stratified by sex only (not pooled); | Dietary patterns at age(s):40 years and older; Food Compass Score (FCS) [Mozzafarrian, 2021]; UPF (Nova food classification system, group 4 [Monteiro, 2019]); [underlined: UPF, FCS] (Nova 4, 20 items w/ beverages): Ramen; Dumpling/dumpling with soup; Corn flakes; Loaf of bread, sandwich, toast; Bread with few red beans; Other bread; Cakes/chocolate pie; Parched grains powder (pre-eating); Cookies/crackers/snacks; Candy/chocolate; Pizza/hamburger; Ham/sausage; Fish paste/ crab flavoring; Yogurt; Ice cream; Soy milk; Coffee; Green tea; Carbonated drinks; Other drinks.; [underlined: UPF, Nova 4] (14 items excluded beverages): Ramen; Dumpling/dumpling with soup; Corn flakes; Loaf of bread, sandwich, toast; Bread with few red beans; Other bread; Cake; Parched grains powder (pre-eating); Cookies; Candy; Pizza; Ham; Flavored crab; Ice cream.; Nova 3 e.g., noodles, kimchi; Nova 1+ 2: e.g., raw, fresh, frozen vegetables, fruit, legumes, rice, etc. + 3 processed culinary ingredients: jam, sugar, cream; Method: Index/Score Analysis | F/U: 5 years; FCS & Risk of Obesity; - ♂ Q2 (more UPF), HR: 1.228, 95% CI: 0.928, 1.626; - ♂ Q3, HR: 1.052, 95% CI: 0.786, 1.408; - ♂ Q4 (less UPF), HR: 0.898, 95% CI: 0.662, 1.219; p-trend=0.3037; - ♀ Q2 (more UPF), HR: 0.996, 95% CI: 0.832, 1.193; - ♀ Q3, HR: 0.878, 95% CI: 0.731, 1.053; - ♀ Q4 (less UPF), HR: 0.759, 95% CI: 0.628, 0.916; p=0.007; Nova 4 & Risk of Obesity; - ♂, g, Q2, HR: 0.826, 95% CI: 0.608, 1.121; - ♂, g, Q3, HR: 1.002, 95% CI: 0.733, 1.371; - ♂, g, Q4, HR: 1.037, 95% CI: 0.728, 1.478; p=0.4126; - ♂, % g, Q2, HR: 1.060, 95% CI: 0.780, 1.442; - ♂, % g, Q3, HR: 1.035, 95% CI: 0.749, 1.430; - ♂, % g, Q4, HR: 1.340, 95% CI: 0.936, 1.918; p=0.0868; - ♀ g, Q2, HR: 1.071, 95% CI: 0.887, 1.292; - ♀ g, Q3, HR: 1.132, 95% CI: 0.925, 1.386; - ♀ g, Q4, HR: 1.360, 95% CI: 1.072, 1.725; p=0.0087; - ♀ % g, Q2, HR: 0.994, 95% CI: 0.823, 1.200; - ♀ % g, Q3, HR: 1.196, 95% CI: 0.980, 1.459; - ♀ % g, Q4, HR: 1.508, 95% CI: 1.191, 1.909; p=0.0001; Nova 4 & BMI:; - ♂, g, β: 0.002, 95% CI: 0.001, 0.003; p=0.0026; - ♂,% g, β: 0.027, 95% CI: 0.010, 0.043; p=0.0022; - ♀, g, β: 0.001, 95% CI: 0.000, 0.002; p=0.0016; - ♀, % g, β: 0.017, 95% CI: 0.006, 0.027; p=0.0024; Nova 3, g/d & Risk of Obesity; - ♂, g, Q2, HR: 1.038, 95% CI: 0.759, 1.420; - ♂, g, Q3, HR: 1.332, 95% CI: 0.971, 1.826; - ♂, g, Q4, HR: 0.982, 95% CI: 0.689, 1.399; p=0.9186; - ♀, g, Q2, HR: 0.984, 95% CI: 0.812, 1.193; - ♀, g, Q3, HR: 1.041, 95% CI: 0.857, 1.265; - ♀, g, Q4, HR: 1.034, 95% CI: 0.839, 1.274; p=0.6476; Nova 1+2, g/d & Risk of Obesity; - ♂, g, Q2, HR: 1.201, 95% CI: 0.892, 1.619; - ♂, g, Q3, HR: 1.211, 95% CI: 0.880, 1.667; - ♂, g, Q4, HR: 0.974, 95% CI: 0.669, 1.418; p=0.5701; - ♀, g, Q2, HR: 0.82, 95% CI: 0.678, 0.990; - ♀, g, Q3, HR: 0.815, 95% CI: 0.925, 1.00; - ♀, g, Q4, HR: 0.716, 95% CI: 0.565, 0.907; p=0.0201 | - Did not account for: Race/ethnicity (Korean); - Diet assessed via FFQ at baseline and F/U (avg. used); Misclassification possible due to UPF intake based on FFQ; Q4 UPF also had lowest aMED scores; Outcome methods calculated BMI but did NR if weight/height was measured or reported; Funding: National Genome Research Institute, Korea Centers for Disease Control and Prevention

a Abbreviations: BMI, body mass index; DM, Diabetes mellitus; DXA, Dual-energy X-ray absorptiometry; FFM, Fat-free mass; FFMI, Fat-free mass index; FFQ, Food frequency questionnaire; FM, Fat mass (total, unless specified); FMI, Fat mass index; F/U, Follow-up; ITT, intent-to-treat; LFU, lost to follow-up; N/A, Not applicable; NR, not reported; OR, odds ratio; PP, per-protocol; Q, quantile; SEP/SES, Socioeconomic position/status; T, tertile; T2D, Type 2 Diabetes; UPF, Ultra-processed food; WC, waist circumference; ♂ male; ♀ female

Table 13 Risk of bias for interventions examining dietary patterns with varying amounts of ultra-processed food consumed by adults and older adults and growth, body composition and risk of obesity^*^ * Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, Elbers RG, Blencowe NS, Boutron I, Cates CJ, Cheng H-Y, Corbett MS, Eldridge SM, Hernán MA, Hopewell S, Hróbjartsson A, Junqueira DR, Jüni P, Kirkham JJ, Lasserson T, Li T, McAleenan A, Reeves BC, Shepperd S, Shrier I, Stewart LA, Tilling K, White IR, Whiting PF, Higgins JPT. RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898 31462531 .

Article | Randomization | Deviations from intended interventions (effect of assignment) | Deviations from intended interventions (per-protocol) | Missing data | Outcome measurement | Selection of the reported result | Overall
Calvo-Malvar, 2021 ^32^ | LOW | LOW | SOME CONCERNS | LOW | LOW | HIGH | SOME CONCERNS

Table 14 Risk of bias for observational studies examining dietary patterns with varying amounts of ultra-processed food consumed by adults and older adults and growth, body composition and risk of obesity^a^

Article | Confounding | Exposure classification | Participant Selection | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall
Beslay, 2020^31^ | Low | Low | Some concerns | Low | Some concerns | High | Low | High
Canhada, 2019^33^ | Some concerns | Some concerns | Some concerns | Low | Some concerns | Low | Low | Some concerns
Canhada, 2023^34^ | Low | High | Some concerns | Low | Some concerns | Low | High | High
Cordova, 2021^35^ | Low | Some concerns | Some concerns | Low | Some concerns | High | Some concerns | High
González-Palacios36 | High | High | Some concerns | Some concerns | Low | Low | Some concerns | High
Konieczna, 2021^37^ | Low | Some concerns | Some concerns | Some concerns | Some concerns | Low | Some concerns | High
Li, 2021^38^ | High | Some concerns | Low | Low | Some concerns | Low | Some concerns | High
Livingstone, 2022^39^ | Low | Low | Some concerns | Low | Some concerns | Low | Some concerns | Some concerns
Mendonca, 2016^40^ | Some concerns | High | Some concerns | Low | Low | High | Some concerns | High
Mirmiran 2022^41^ | High | High | Some concerns | Low | High | Low | Some concerns | High
Pant, 2023^42^ | Some concerns | High | Low | Low | Some concerns | High | Some concerns | High
Rauber, 2021^43^ | Some concerns | Some concerns | Low | Low | High | Low | Some concerns | High
Rudakoff, 2022^44^ | High | High | Some concerns | Low | Some concerns | Low | Some concerns | High
Santos, 2023^45^ | High | Some concerns | Low | Low | Some concerns | High | Low | High
Tan 2023^46^ | Some concerns | High | Low | Low | High | High | Very high | Very high

a Possible ratings of low, some concerns, high, very high, not applicable, or no information no information determined using the “Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)” tool ( ROBINS-E Development Group Higgins J, Morgan R, Rooney A, . Risk Of Bias In Non-randomized Studies - of Exposure (ROBINS-E). Launch version, 1 June 2022. Available from: https://www.riskofbias.info/welcome/robins-e-tool. ) *Low risk of bias except for concerns about uncontrolled confounding.

## Pregnancy and postpartum

Two articles met the inclusion criteria examining the relationship between dietary patterns with varying amounts of UPF consumed during pregnancy and/or postpartum and gestational weight gain and postpartum weight change. Both articles analyzed prospective cohort studies.^47,48^

### Description of the evidence

#### Population

One study was conducted in the United States^47^ and another one in Brazil^48^ and included 367 and 584 participants, respectively. Both articles included >50% of the participants with overweight and obesity and Dias and colleagues, included only participants with gestational diabetes mellitus.^48^ Cummings and colleagues, noted that participants were 17% “Black”, 5.3% “Asian”, 6.3% “Other or multiracial”, and 8.6% Hispanic and income-poverty ratio of 3.84.^47^ Dias and colleagues, reported that 49% of the participants were non-White and 21% of the participants had family income below minimum wage.^48^

#### Intervention/exposure and comparator

Cummings and colleagues^47^ collected dietary data using 24-hour dietary recall at multiple time-points during pregnancy and postpartum period and examined scores on the “Instant” dietary pattern comprised of ready-to-heat pre-prepared pies, pasta, and pizza dishes; mass-produced packaged breads; reconstituted meats; sweet or savory packaged snacks; confectionery desserts; sweetened drinks. Dias and colleagues^48^ used a brief food-frequency questionnaire to collect dietary data during pregnancy and 6-mo postpartum periods and derived the “Risk” dietary pattern from factor/cluster analysis comprised of Fried foods; Cookies and sweets; Sweetened beverages; Processed meat; Red meat with visible fat.

#### Outcomes

Cummings and colleagues assessed weight during pregnancy and categorized gestational weight gain as inadequate, adequate or excessive, based on 2009 Institute of Medicine guidelines^*^. Postpartum weight change was defined as the change in weight between baseline (<12 weeks of pregnancy) and one year postpartum, both measured by the investigators. Percent of gestational weight gain retained was calculated by multiplying 100 by the difference in weight between the last prenatal medical visit (investigator measured) and one year postpartum (investigator measured), divided by gestational weight gain. Dias et al. reported the variation in BMI between 2-mo and 12-mo postpartum. These outcome measures were calculated based on the self-reported weight by the participants.

* Institute of Medicine. Weight gain during pregnancy: reexamining the guidelines. Washington, DC: National Academies Press; 2009

### Synthesis of the evidence

#### Pregnancy

One study assessed the association between dietary patterns with varying amounts of UPF and gestational weight gain. The authors reported that a dietary pattern with greater amounts of foods classified as UPF (per SD) during pregnancy was significantly associated with higher risk of excessive gestational weight gain, but not significantly associated with the risk of inadequate gestational weight gain.

#### Postpartum

Two studies reported that there was no association between consumption of dietary patterns with UPF during postpartum and either % gestational weight gain retained and postpartum weight change^47^ or with BMI at 12 months postpartum^48^

### Conclusion statement and grade

Insufficient evidence is available to adequately assess the body of evidence for consistency, directness, risk of bias (see Table 17), precision, and generalizability. This body of evidence is less likely to have publication bias as it includes only 2 studies with mixed and/or null findings from relatively small sample sizes.

Table 15 Conclusion statement, grades dietary patterns with varying amounts of ultra-processed food consumed during pregnancy and gestational weight gain

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between dietary patterns consumed during pregnancy with varying amounts of ultra-processed food and gestational weight gain because there is not enough evidence available
Grade | Grade not assignable
Body of Evidence | 1 article from a prospective cohort study
Rationale | The body of evidence cannot be adequately assessed due to too few studies meeting criteria for inclusion.

Table 16 Conclusion statement, grades dietary patterns with varying amounts of ultra-processed food consumed during postpartum and postpartum weight change

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between dietary patterns consumed during postpartum with varying amounts of ultra-processed food and postpartum weight change because there is not enough evidence available.
Grade | Grade not assignable
Body of Evidence | 2 articles from prospective cohort studies
Rationale | The body of evidence cannot be adequately assessed due to too few studies meeting criteria for inclusion.

Table 17 Studies examining the relationship between dietary patterns with varying amounts of ultra-processed food consumed during pregnancy and postpartum and postpartum and gestational weight gain and postpartum weight change.^i^* * Abbreviations: FFQ, Food frequency questionnaire; GDM, Gestational diabetes mellitus; GWG, Gestational weight gain; PPWR, Postpartum weight retention; PPWC, Postpartum weight change; TEI, total energy intake; UPF, ultra-processed food

Article Information | Intervention/exposure and comparator | Results | Methodological considerations
Cummings, 2022^47^; PCS, United States, PEAS; Analytic N=321; - Age (y): 30.5±4.7; - Smoking (%): Current: 2; Former: 18 Race/Ethnicity (%): White: 71; Black: 17, Asian: 5, Other or multiracial: 6; Hispanic: 9; - Socioeconomic position: Income-Poverty Ratio: 3.84±1.97; - Education (%): College degree: 72; - Pre-pregnancy BMI (%): <18.5: 0.0; ≥25: 25.1; >30: 27.1; - GWG (%): Inadequate: 19; Adequate: 34; Excessive: 47 | UPF (Nova food classification system, group 4 [Monteiro, 2019^1])^]) (continuous adherence, % TEI z-scored); ASA24 at: <12 weeks, 16-22 weeks, 28-32 weeks gestation, ~2 months, 6 months, 1y postpartum; Dietary pattern description: Positive: ‘instant’ foods; ready-to-heat pre-prepared pies, pasta, and pizza dishes; mass-produced packaged breads; reconstituted meats; sweet or savory packaged snacks; confectionery desserts; sweetened drinks; Outcome and assessment methods: GWG, PPWR, PPWC assessed at ~1y postpartum. GWG categorized as inadequate, adequate and excessive, based on IOM (2009) recommendations. PPWR (%) calculated as difference in weight from last prenatal medical visit to 1y postpartum divided by GWG, multiplied by 100. PPWC (kg) calculated by subtracting weight at baseline (<12 GW) from weight at 1y postpartum Weight, height measured by investigators, and from prenatal medical records. | GWG, OR, % per-SD UPF during pregnancy; Inadequate: 0.88, 95% CI: 0.63, 1.23, p=0.45; Excessive: 1.31, 95% CI: 1.01, 1.70, p=0.045; PPWR, Linear regression, % per-SD UPF during postpartum, β±SE (95% CI) −4.33±3.39 (−11, 2.34), p=0.202; PPWC, Linear regression, kg per-SD UPF during postpartum; β±SE (95% CI) −0.44±0.36 (−1.14, 0.27), p=0.222 | Key confounders accounted for: Age, Physical activity, Pre-pregnancy BMI and/or GWG (PPWR only), Socioeconomic position, Smoking status; Key confounders not accounted for: Race/ethnicity, Parity, Human milk feeding status; Other covariates: TEI, time; Limitations: Issues with confounding and some concerns with exposure measurement, missing data and selection of reported result; Funding: NICHD, NIH
Dias, 2023^48^; PCS, Brazil, LINDA-Brasil; Analytic N=584; - Age (y): 18 y or older (54% 30-39 y); - 100% participants with GDM; - Race/Ethnicity (%):51% White, 49% Non-White; - Socioeconomic position: 23% ≥3 Minimum wage (highest), 25% 2 to <3, 37% 1 to <2, 15% <1 (lowest);; - 92% living with partner; - Pre-pregnancy BMI: 42% Ob, 39% OW, 19%; - Postpartum 2-months F/U: 42% Obesity, 44% Overweight, 14% Normal/Underweight; - Excessive GWG: 21.5%, Adequate GWG, 25.3%, Insufficient GWG 53.2% | ‘Risk’ dietary pattern (tertiles); Short-FFQ, applied during pregnancy and postpartum (6-months); Dietary pattern description: Positive: Fried foods; Cookies and sweets; Sweetened beverages; Processed meat; Red meat with visible fat; Outcome and assessment methods: Variation in BMI between 2- and 12-months postpartum, based on self-reported weight | Change in BMI, 12 months postpartum; T1: Ref; T2: 1.09, 95% CI: 0.86, 1.38; T3, 1.09, 95% CI: 0.86, 1.37 | Key confounders accounted for: Age, Sex, Alcohol intake, Race and/or ethnicity, Socioeconomic position, Anthropometry, Smoking, Breastfeeding during F/U period; Key confounders not accounted for: Physical activity; Other covariates: Study center, parity; Limitations: 100% GDM participants, self-reported outcomes, misclassification possible due to UPF intake from FFQ, Potential influence of knowledge of 2 months weight measure on postpartum diet assessment; Funding: Brazilian National Council of Technological and Scientific Development; Eli Lilly Non-Communicable Diseases Partners; Financiamento e Incentivo à Pesquisa do Hospital de Clínicas de Porto Alegre

Table 18 Risk of bias for observational studies examining dietary patterns with varying amounts of ultra-processed food consumed during pregnancy and/or postpartum and gestational weight and postpartum weight change.^*^ * Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)” tool (ROBINS-E Development Group ( Higgins J, Morgan R, Rooney A, Taylor K, Thayer K, Silva R, Lemeris C, Akl A, Arroyave W, Bateson T, Berkman N, Demers P, Forastiere F, Glenn B, Hróbjartsson A, Kirrane E, LaKind J, Luben T, Lunn R, McAleenan A, McGuinness L, Meerpohl J, Mehta S, Nachman R, Obbagy J, O’Connor A, Radke E, Savović J, Schubauer-Berigan M, Schwingl P, Schunemann H, Shea B, Steenland K, Stewart T, Straif K, Tilling K, Verbeek V, Vermeulen R, Viswanathan M, Zahm S, Sterne J). Risk Of Bias In Non-randomized Studies - of Exposure (ROBINS-E). Launch version, 1 June 2022. Available from: https://www.riskofbias.info/welcome/robins-e-tool. ) *Low risk of bias except for concerns about uncontrolled confounding.

Article | Confounding | Exposure classification | Participant Selection | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall
Cummings, 2022 ^47^ | High | Some concerns | Low | Low | Some concerns | Low | Some concerns | High
Dias, 2023 ^48^ | Low | Low | Low | Low | High | High | Some concerns | High