# Methods

The Committee used NESR’s methodology to conduct this systematic review. NESR’s methodology is described in detail in its methodology manual,^*^ as well as in the Committee’s scientific report^†^. This section presents an overview of the specific methods used to answer the systematic review question: What is the relationship between consumption of dietary patterns with varying amounts of ultra-processed foods and growth, body composition, and risk of obesity?

* USDA Nutrition Evidence Systematic Review Branch. USDA Nutrition Evidence Systematic Review: Methodology Manual. February U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://nesr.usda.gov/methodology-overview

† 2025 Dietary Guidelines Advisory Committee. 2024. Scientific Report of the 2025 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Health and Human Services and Secretary of Agriculture. U.S. Department of Health and Human Services. 10.52570/DGAC2025

## Develop a protocol

A systematic review protocol is the plan for how NESR’s methodology is used to conduct a specific systematic review and is established by the Committee, a priori, before any evidence is reviewed. The protocol is designed to capture the most appropriate and relevant body of evidence to answer the systematic review question. Development of the protocol involves discussion of the strengths and limitations of various methodological approaches relevant to the question, which then inform subsequent steps of the systematic review process. The protocol describes all of the methods used throughout the systematic review process. Additionally, the protocol includes the following components, which are tailored to each systematic review question: the analytic framework, the inclusion and exclusion criteria, and the synthesis plan.

The protocol was posted online (https://nesr.usda.gov/protocols) for the public to view and comment on. Revisions to the systematic review protocol were made during the review process. These amendments are documented in Table 2.

Table 2 Protocol revisions

Date | Protocol revision | Description
July 2023 | Inclusion and exclusion criteria were added for confounders, specifying that studies must control for at least one key confounder listed in the analytic framework to be included. | This revision was made to enable focus on a stronger body of evidence. The revision was made before any evidence was synthesized.
July 2023 | The inclusion and exclusion criteria for the outcome of gestational weight gain were revised to include only those studies that examine adequacy of total gestational weight gain (i.e., in relation to recommendations based on pre-pregnancy BMI). Studies that examine gestational weight gain during certain time periods or trimesters of pregnancy or total gestational weight gain not in relation to recommendations will be excluded. | This revision was made to focus on the most clinically meaningful measure of gestational weight gain. The revision was made before any evidence was synthesized.
July 2023 | The inclusion and exclusion criteria for the intervention/exposure and comparator were revised to clarify that:; - a study must provide a description of the foods and beverages in both the intervention/exposure and comparator groups to be included.; - studies that examine consumption of and/or adherence to similar dietary patterns of which only a specific component or food source differs between groups are excluded. | These revisions were made before evidence synthesis to clarify the intent of the intervention/exposure and comparator criteria, but do not represent a change in how the criteria were applied.
September 2023 | The inclusion criteria for study duration for weight loss and weight loss maintenance was reduced from ≥6 months and 12 months, respectively, to ≥12 weeks. | This revision was made so that study duration criteria is consistent across all growth, body composition, and risk of obesity outcomes. Longer-term studies on weight loss and weight loss maintenance will be prioritized in evidence synthesis. The revision was made before any evidence was synthesized.
September 2023 | The exclusion criteria for outcome were revised to specify that studies that only report unintentional weight loss (i.e., a component of frailty) will be excluded. | This revision was made to clarify the intent of the outcome criteria but does not represent a change in how the criteria were applied.
January 2024 | The inclusion and exclusion criteria for the intervention/exposure and comparator were revised to clarify the comparisons of interest are:; - Consumption of a dietary pattern with ultraprocessed foods (UPF) compared to a dietary pattern without UPF; - Different adherence to/consumption levels of the same dietary pattern that reflect differences in the amount of UPF | This revision was made to better determine the effect of different amounts of UPF in dietary patterns on outcomes. This revision was made before any evidence was synthesized for this question.
January 2024 | The inclusion and exclusion criteria for the publication date were revised to correct the search date range of literature is January 2000 to January 2024. | This revision was to update an error in the original protocol.

## Develop an analytic framework

An analytic framework visually represents the overall scope of the systematic review question and depicts the contributing elements that were examined and evaluated. It presents the core (PICO) elements of each systematic review question, including the Population (i.e., those who experience the intervention/exposure and/or outcome), Intervention and/or exposure (i.e., the independent variable of interest), Comparator (i.e., the alternative being compared to the intervention or exposure), and Outcome(s). Definitions for key terms are also included because they provide the basis for how concepts are operationalized throughout the review. The Committee identified key confounders based on their knowledge of nutrition and health research and experience as subject matter experts. Key confounders are factors related to both intervention/exposure and the outcome of interest that may impact the estimated effects of interest, such as demographics, health status, and diet and lifestyle behaviors, and/or other factors related to both the intervention/exposure and the outcome of interest that may impact the relationships of interest. Key confounders were considered during review and evaluation of the evidence, particularly during the risk of bias assessment of non-randomized and observational studies.

Figure 1 is the analytic framework for the systematic review and shows that the interventions or exposures and comparators of interest are a) dietary patterns with ultra-processed foods (UPF) compared to dietary patterns without UPF, and b) different levels of adherence to/consumption of the same dietary pattern that reflect differences in the amounts of UPF, consumed by infants, young children up to age 24 months, children, adolescents, adults, older adults, individuals during pregnancy, and individuals during postpartum. The outcomes are growth (in infants, young children up to age 24 months, children, adolescents) including: height, length/stature-for-age, weight, weight-for-age, stunting, failure to thrive, wasting, BMI-for-age, weight-for-length/stature, body circumferences (arm, neck, thigh), head circumference; Body composition (in infants, young children up to age 24 months, children, adolescents, adults, older adults) including: skinfold thickness, fat mass, ectopic fat, fat-free mass or lean mass, waist circumference, waist-to-hip-ratio; Risk of obesity (in children, adolescents, adults, older adults) including: BMI, underweight, normal weight, overweight and/or obesity, weight loss and maintenance (in adults, older adults); Pregnancy and postpartum-related weight change (in individuals during pregnancy or postpartum) including: gestational weight gain and postpartum weight change. The key confounders may impact the relationships of interest and are sex, age, physical activity, anthropometry at baseline, socioeconomic position, race and/or ethnicity in all populations, alcohol intake in adults and older adults, smoking in adults, older adults, during pregnancy and postpartum, parity (pregnancy, postpartum), diabetes mellitus in the current pregnancy (pregnancy), hypertensive disorders in the current pregnancy (pregnancy), and human milk feeding status (postpartum). Dietary patterns are defined as the quantities, proportions, variety, or combination of different foods, drinks, and nutrients (when available) in diets, and the frequency with which they are habitually consumed.

Figure 1 Analytic framework for the systematic review question: What is the relationship between consumption of dietary patterns with varying amounts of ultra-processed foods and growth, body composition, and risk of obesity?

Population | Intervention/ exposure and Comparator | Outcome | Key confounders
Infants and young children up to age 24 months | - Consumption of a dietary pattern with ultra-processed foods (UPF) compared to a dietary pattern without UPF; - Different adherence to/consumption levels of the same dietary pattern that reflect differences in the amount of UPF | Growth (in infants, young children up to age 24 months, children, adolescents); - Height, length/stature-for-age; - Weight, weight-for-age; - Stunting, failure to thrive, wasting; - BMI-for-age, weight-for-length/stature; - Body circumferences (arm, neck, thigh); - Head circumference; Body composition (in infants, young children up to age 24 months, children, adolescents, adults, older adults); - Skinfold thickness; - Fat mass, ectopic fat; - Fat-free mass or lean mass; - Waist circumference, waist-to-hip-ratio; Risk of obesity (in children, adolescents, adults, older adults); - BMI; - Underweight; - Normal weight; - Overweight and/or obesity; - Weight gain; - Weight loss and maintenance (adults, older adults) | - Sex; - Age; - Physical activity; - Race and/or ethnicity; - Socioeconomic position; - Anthropometry at baseline; - Smoking (adults, older adults); - Alcohol intake (adults, older adults)
Children and adolescents (2 up to 19 years) | | | - Sex; - Age; - Physical activity; - Race and/or ethnicity; - Socioeconomic position; - Anthropometry at baseline; - Smoking (adults, older adults); - Alcohol intake (adults, older adults)
Adults and older adults (19 years and older) | | | - Sex; - Age; - Physical activity; - Race and/or ethnicity; - Socioeconomic position; - Anthropometry at baseline; - Smoking (adults, older adults); - Alcohol intake (adults, older adults)
Individuals during pregnancy and postpartum | - Consumption of a dietary pattern with UPF compared to a dietary pattern without UPF; - Different adherence to/consumption levels of the same dietary pattern that reflect differences in the amount of UPF | Pregnancy and postpartum-related weight change (in individuals during pregnancy or postpartum); - Gestational weight gain; - Postpartum weight change | - Age; - Physical activity; - Race and/or ethnicity; - Socioeconomic position; - Anthropometry at baseline; - Smoking; - Parity; - Diabetes mellitus in the current pregnancy (pregnancy); - Hypertensive disorders in the current pregnancy (pregnancy); - Human milk feeding status (postpartum)

Synthesis organization:

I. Population: Infants and young children up to age 24 months; Children and adolescents; Adults; Older adults; Individuals during pregnancy; Individuals during postpartum
  i. Outcome: Growth; Body composition; Risk of obesity; Weight loss and maintenance; Pregnancy and postpartum-related weight change

Key definitions: [underlined: Dietary patterns:] the quantities, proportions, variety, or combination of different foods, drinks, and nutrients (when available) in diets, and the frequency with which they are habitually consumed.

## Develop inclusion and exclusion criteria

The inclusion and exclusion criteria provide an objective, consistent, and transparent framework for determining which articles to include in the systematic review (Table 3). These criteria ensure that the most relevant and appropriate body of evidence is identified for the systematic review question, and that the evidence reviewed is^*^:

- Applicable to the U.S. population of interest
- Relevant to Federal public health nutrition policies and programs
- Rigorous from a scientific perspective

* USDA Nutrition Evidence Systematic Review Branch. USDA Nutrition Evidence Systematic Review: Methodology Manual. February 2023. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://nesr.usda.gov/methodology-overview

Table 3 Inclusion and exclusion criteria

Category | Inclusion Criteria | Exclusion Criteria
Study | - Randomized controlled trials; - Non-randomized controlled trials^†^; † Including quasi-experimental and controlled before-and-after studies; - Prospective cohort studies; - Retrospective cohort studies; - Nested case-control studies | - Uncontrolled trials^‡^; ‡ Including uncontrolled before-and-after studies; - Case-control studies; - Cross-sectional studies; - Ecological studies; - Narrative reviews; - Systematic reviews; - Meta-analyses; - Modeling and simulation studies
Publication date | - January 2000 – January 2024 | - Before January 2000, after January 2024
Population: Study participants | - Human | - Non-human
Population: Life stage | At intervention or exposure and outcome:; - Infants and young children up to age 24 months; - Children and adolescents (2 up to 19 years); - Adults and older adults (19 years and older); - Individuals during pregnancy; - Individuals during postpartum | At intervention or exposure and outcome:; - Individuals before pregnancy
Population: Health status | - Studies that [underlined: exclusively] enroll participants not diagnosed with a disease^*^; * Studies that enroll participants who are at risk for chronic disease were included; - Studies that enroll [underlined: some] participants:; ○ diagnosed with a disease;; ○ with severe undernutrition, failure to thrive/underweight, stunting, or wasting;; ○ born preterm,^†^ with low birth weight,^‡^ and/or small for gestational age;; † Gestational age <37 weeks and 0/7 days; ‡ Birth weight <2500g; ○ and/or with the outcome of interest; ○ who became pregnant using Assisted Reproductive Technologies;; ○ with multiple gestation pregnancies;; ○ pre- or post-bariatric surgery;; ○ and/or receiving pharmacotherapy to treat obesity | - Studies that [underlined: exclusively] enroll participants:; ○ diagnosed with a disease;^§^; § Studies that exclusively enroll participants with obesity were included; ○ hospitalized for an illness, injury, or surgery;^**^; ** Studies that exclusively enroll participants post-cesarean section were included; ○ with severe undernutrition, failure to thrive/underweight, stunting, or wasting;; ○ born preterm,^†^ with low birth weight,^‡^ and/or small for gestational age; ○ who became pregnant using Assisted Reproductive Technologies;; ○ with multiple gestation pregnancies;; ○ pre- or post-bariatric surgery;; ○ and/or receiving pharmacotherapy to treat obesity
Intervention/ exposure | - Studies that examine consumption of and/or adherence to a dietary pattern [i.e., the quantities, proportions, variety, or combination of different foods, drinks, and nutrients (when available) in diets, and the frequency with which they are habitually consumed] with varying amounts of ultraprocessed foods (UPF), including, at a minimum, a description of the foods and beverages in the pattern of each intervention/exposure and comparator group; ○ Dietary patterns may be measured or derived using a variety of approaches, such as adherence to a priori patterns (indices/scores), data driven patterns (factor or cluster analysis), reduced rank regression, or other methods, including clinical trials; - Multi-component intervention in which the isolated effect of the dietary pattern with varying amounts of ultra-processed foods on the outcome(s) of interest is provided or can be determined | - Studies that do not provide a description of the dietary pattern, which at minimum, must include the foods and beverages in the pattern (i.e., studies that examine a labeled dietary pattern, but do not describe the foods and beverages consumed in each intervention/exposure and comparator group); - Studies that examine consumption of and/or adherence to a dietary pattern(s) of which the amount of or definition of UPF cannot be determined.; - Multi-component intervention in which the isolated effect of the intervention of interest on the outcome(s) of interest is not provided or cannot be determined (e.g., due to multiple intervention components within groups)
Comparator | - Studies that compare a dietary pattern with UPF compared to a dietary pattern without UPF; - Different levels of consumption of and/or adherence to the same dietary pattern that reflect differences in the amount of UPF | - Consumption of and/or adherence to a similar dietary pattern of which only a specific component or food source differs between groups and/or the different amounts of or definition of UPF cannot be determined,
Outcome(s) | - Growth (in infants, young children up to age 24 months, children, adolescents); ○ Height, length/stature-for-age; ○ Weight, weight-for-age; ○ Stunting, failure to thrive, wasting; ○ BMI-for-age, weight-forlength/stature; ○ Body circumferences (arm, neck, thigh); ○ Head circumference; - Body composition (in infants, young children up to age 24 months, children, adolescents, adults, older adults); ○ Skinfold thickness; ○ Fat mass, ectopic fat; ○ Fat-free mass or lean mass; ○ Waist circumference, waist-to-hip-ratio; - Risk of obesity (in children, adolescents, adults, older adults); ○ BMI; ○ Underweight; ○ Normal weight; ○ Overweight and/or obesity; ○ Weight gain; ○ Weight loss and maintenance (in adults, older adults); - Pregnancy and postpartum-related weight change (in individuals during pregnancy or postpartum); ○ Adequacy of total gestational weight gain (i.e., in relation to recommendations based on pre-pregnancy BMI); ○ Postpartum weight change | - Gestational weight gain only during certain time periods or trimesters of pregnancy; - Absolute total gestational weight gain (i.e., not in relation to recommendations based on pre-pregnancy BMI); - Weight loss that is specifically classified as unintentional weight loss (e.g., a component of frailty)
Confounders | - Studies that control for at least one of the key confounders listed in the analytic framework | - Studies that do not control for any of the key confounders listed in the analytic framework
Study duration (not applied to pregnancy and postpartum studies) | - Intervention length ≥12 weeks | - Intervention length <12 weeks
Size of study groups (not applied to pregnancy and postpartum studies) | - For intervention studies:; ○ ≥30 participants per study group for between-subject analyses,; ○ or a power calculation indicating that the study is appropriately powered for the outcome(s) of interest; - For observational studies:; ○ Analytic sample size of ≥1000 participants (only for adults and older adults) | - For intervention studies:; ○ <30 participants per study group for between-subject analyses,; ○ and no power calculation indicating that the study is appropriately powered for the outcome(s) of interest; - For observational studies:; ○ Analytic sample size n<1000 (only for adults and older adults)
Publication status | - Peer-reviewed articles published in research journals | - Non-peer reviewed articles, unpublished data or manuscripts, pre-prints, reports, and conference abstracts or proceedings
Language | - Published in English | - Not published in English
Country^*^; * The classification of countries on the Human Development Index (HDI) is based on the UN Development Program Human Development Report Office (http://hdr.undp.org/en/data) for the year the study intervention occurred or data were collected. Studies conducted prior to 1990 are classified based on 1990 HDI classifications. If the year is more recent than the available HDI values, then the most recent HDI classifications are used. If a country is not listed in the HDI, then the current country classification from the World Bank is used (The World Bank. World Bank country and lending groups. Available from: https://datahelpdesk.worldbank.org/knowledgebase/articles/906519-world-country-and-lending-groups) | - Studies conducted in countries classified as high or very high on the Human Development Index the year(s) the intervention/exposure data were collected | - Studies conducted in countries classified as medium or low on the Human Development Index the year(s) the intervention/exposure data were collected

## Search for and screen studies

NESR librarians, in collaboration with NESR analysts and the Committee, used the analytic framework and inclusion and exclusion criteria to develop a comprehensive literature search strategy. The literature search strategy included selecting and searching the appropriate bibliographic databases, translating search terms using syntax appropriate for the databases being searched, and employing search refinements, such as search filters. The full literature search strategy is documented in Appendix 3.

The results of all electronic database searches, after removal of duplicates, were screened independently by two NESR analysts using a stepwise process of reviewing titles, abstracts, and full texts to identify articles meeting the inclusion criteria. Manual searching was conducted to find peer-reviewed published articles not identified through the electronic database search. These articles were also screened independently by two NESR analysts at the abstract and full-text levels.

## Extract data and assess the risk of bias

NESR analysts extracted all essential data from each included article to describe key characteristics of the available evidence, such as the author, publication year, cohort/trial name, study design, population life stage at intervention/exposure and outcome, intervention/exposure and outcome assessment methods, and outcomes. One NESR analyst extracted the data and a second NESR analyst reviewed the extracted data for accuracy. Each article included in the systematic review underwent a formal risk of bias assessment, with two NESR analysts independently completing the risk of bias assessment using the tool that is appropriate for the study design.^*^,^†^,^‡§^

* Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ. 2019; 366: l4898.doi:10.1136/bmj.l4898 31462531

† Sterne JAC, Hernán MA, Reeves BC . ROBINS-I: a tool for assessing risk of bias in non-randomized studies of interventions. BMJ. 2016; 355; i4919; doi: 10.1136/bmj.i4919 27733354

‡ Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602.

## Synthesize the evidence

The Committee described, compared, and combined the evidence from all included studies to answer the systematic review question. Synthesis of the body of evidence involved identifying overarching themes or key concepts from the findings, identifying and explaining similarities and differences between studies, and determining whether certain factors impact the relationships being examined, which includes potential causes of heterogeneity across all included evidence.

Extracted data and risk of bias assessments for all included studies were tabulated to visually display results and facilitate synthesis. During synthesis, the Committee considered the effect direction, magnitude, and statistical significance of the results reported across the articles included in the body of evidence. The evidence was synthesized qualitatively without meta-analysis of effect estimates, statistical pooling or conversion of data, or quantitative tests of heterogeneity.

The synthesis plan for this review was designed with the end-use in mind, to inform the Committee’s advice to HHS and USDA regarding dietary guidance across life stages. The first level of synthesis organization was by population at intervention or exposure. Then, the evidence was considered based on similar outcomes across the available evidence.

## Develop a conclusion statement and grade the evidence

After the Committee synthesized the body of evidence, they drafted a conclusion statement. A conclusion statement is one or more summary statements carefully constructed to answer the systematic review question. Each conclusion statement reflects the evidence reviewed, as outlined in the analytic framework (e.g., PICO elements) and synthesis plan, and does not take evidence from other sources into consideration. Conclusion statements do not draw implications and should not be interpreted as dietary guidance. The Committee reviewed, discussed, and revised the conclusion statement until they reached consensus on wording that accurately reflected the body of evidence.

The Committee then graded the strength of the evidence underlying each conclusion statement using NESR’s predefined criteria for five grading elements: consistency, precision, risk of bias, directness and generalizability of the evidence. Study design and publication bias were also considered.^*^

* Spill MK, English LK, Raghavan R, . Perspective: USDA Nutrition Evidence Systematic Review Methodology: Grading the Strength of Evidence in Nutrition- and Public Health-Related Systematic Reviews. Adv Nutr. 2022 Aug 1;13(4):982–991. doi: 10.1093/advances/nmab147 34918032

- [underlined: Consistency]: Consistency considers the degree of similarity in the direction and magnitude of effect across the body of evidence. This element also considers whether differences across the results can be explained by variations in study designs and methods.
- [underlined: Precision]: Precision considers the degree of certainty around an effect estimate for a given outcome. This element considers measures of variability, such as the width and range of confidence intervals, the number of studies, and sample sizes, within and across studies.
- [underlined: Risk of bias]: Risk of bias considers the likelihood that systematic errors resulting from the design and conduct of the studies could have impacted the accuracy of the reported results across the body of evidence.
- [underlined: Directness]: Directness considers the extent to which studies are designed to directly examine the relationship among the interventions/exposures, comparators, and outcome(s) of primary interest in the systematic review question.
- [underlined: Generalizability:] Generalizability considers whether the study participants, interventions and/or exposures, comparators, and outcomes examined in the body of evidence are applicable to the U.S. population of interest for the review.

The Committee assigned an overall grade to each conclusion statement from the following options: strong, moderate, limited, or grade not assignable. The grade communicates the strength of the evidence supporting a specific conclusion statement to decision makers and stakeholders. A conclusion statement can receive a grade of Strong, Moderate, or Limited, and if insufficient or no evidence is available to answer a systematic review question, then no grade is assigned (i.e., Grade Not Assignable) (Table 4). The overall grade is not based on a predefined formula for scoring or tallying ratings of each element. Rather, each overall grade reflects the expert group’s thorough consideration of all of the grading elements, as they each relate to the specific nuances of the body of evidence under review.

Table 4 Definitions of NESR grades

Grade | Definition
Strong | The conclusion statement is based on a strong body of evidence as assessed by consistency, precision, risk of bias, directness, and generalizability. The level of certainty in the conclusion is strong, such that if new evidence emerges, modifications to the conclusion are unlikely to be required.
Moderate | The conclusion statement is based on a moderate body of evidence as assessed by consistency, precision, risk of bias, directness, and generalizability. The level of certainty in the conclusion is moderate, such that if new evidence emerges, modifications to the conclusion may be required.
Limited | The conclusion statement is based on a limited body of evidence as assessed by consistency, precision, risk of bias, directness, and generalizability. The level of certainty in the conclusion is limited, such that if new evidence emerges, modifications to the conclusion are likely to be required.
Grade Not Assignable | A conclusion statement cannot be drawn due to either a lack of evidence, or evidence that has severe limitations related to consistency, precision, risk of bias, directness, and generalizability.

## Recommend future research

The Committee identified and documented research gaps and methodological limitations throughout the systematic review process. These gaps and limitations are used to develop research recommendations that describe the research, data, and methodological advances that are needed to strengthen the body of evidence on a particular topic. Rationales for the necessity of additional or stronger research are provided with the research recommendations.

## Peer review

This systematic review underwent external peer review in a process coordinated by staff from the National Institutes of Health (NIH). NIH staff identified potential peer reviewers through outreach to a variety of professional organizations to select academic reviewers from U.S. colleges and universities across the country with a doctorate degree, including MDs, and expertise specific to the questions being reviewed. All peer reviewers were external to the Dietary Guidelines process, and therefore, current Committee members or Federal staff who supported the Committee or the development of the Dietary Guidelines were not eligible to serve as peer reviewers.

The peer review process was anonymous and confidential in that the peer reviewers were not identified to the Committee members or NESR staff, and in turn, the reviewers were asked not to share or discuss the review with anyone. Peer reviewers were made aware that per USDA, FNS agency policy, all peer reviewer comments would be summarized and made public, but comments would not be attributed to a specific reviewer.

Peer review occurred after draft conclusion statements were discussed by the full Committee at its third, fourth, fifth, and sixth public meetings. NIH staff assigned and distributed the reviews to at least 2 peer reviewers based on area of expertise. Following peer review, the Committee reviewed and discussed comments and made revisions to the systematic review, as needed, based on the discussion.

## Health equity considerations

The Committee was charged by HHS and USDA to review all scientific questions with a health equity lens to ensure that the next edition of the Dietary Guidelines is relevant to people with diverse racial, ethnic, socioeconomic, and cultural backgrounds. The Committee made a number of health equity considerations throughout the NESR systematic review process. The Committee’s Scientific Report^*^ includes a more detailed discussion of their approach to applying a health equity lens to their review of evidence, but examples of how the Committee incorporated health equity considerations into its systematic reviews and evidence scan include consideration of key confounders relevant to health equity and assessment of generalizability of the evidence.

* 2025 Dietary Guidelines Advisory Committee. 2024. Scientific Report of the 2025 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Health and Human Services and Secretary of Agriculture. U.S. Department of Health and Human Services. 10.52570/DGAC2025