# Plain-language summary

### What is the question?

The question is: What is the relationship between consumption of dietary patterns with varying amounts of ultra-processed foods and growth, body composition, and risk of obesity? The population of interest included infants and young children up to age 24 months, children and adolescents, adults and older adults, individuals during pregnancy, and individuals during postpartum.

### Why was this question asked?

This systematic review was conducted by the 2025 Dietary Guidelines Advisory Committee as part of the process to develop the Dietary Guidelines for Americans, 2025-2030.

### How was this question answered?

The Committee conducted a new systematic review to answer this question with support from the USDA Nutrition Evidence Systematic Review team.

### What is the answer to the question?

#### Infants and Young Children up to age 24 months

- A conclusion statement cannot be drawn about the relationship between dietary patterns consumed by infants and young children up to age 24 months with varying amounts of ultra-processed food and growth, body composition, and risk of obesity because of substantial concerns with consistency and directness in the body of evidence.

#### Children and Adolescents

- Dietary patterns consumed by children and adolescents with higher amounts of foods classified as ultra-processed food are associated with greater adiposity (fat mass, waist circumference, BMI) and risk of overweight. This conclusion statement is based on evidence grade as limited.

#### Adults and Older Adults

- Dietary patterns consumed by adults and older adults with higher amounts of foods classified as ultra-processed food are associated with greater adiposity (fat mass, waist circumference, BMI) and risk of obesity and/or overweight. This conclusion statement is based on evidence grade as limited.

#### Pregnancy

- A conclusion statement cannot be drawn about the relationship between dietary patterns with varying amounts of ultra-processed food consumed during pregnancy and gestational weight gain because there is not enough evidence available.

#### Postpartum

- A conclusion statement cannot be drawn about the relationship between dietary patterns with varying amounts of ultra-processed food consumed during postpartum and body composition, and risk of obesity because there is not enough evidence available.

### How up-to-date is this systematic review?

Conclusion statement(s) from this review are based on articles published between January 2000 and January 2024