# Appendix 3 Excluded articles

The following table lists the articles excluded after full-text screening for this systematic review question. At least one reason for exclusion is provided for each article, though this may not reflect all possible reasons. Information about articles excluded after title and abstract screening is available upon request.

Table A 5 List of excluded articles

Number | Citation | Rationale
1 | Acosta-Navarro JC, Oki AM, Antoniazzi L, et al. Consumption of animal-based and processed food associated with cardiovascular risk factors and subclinical atherosclerosis biomarkers in men. Article. Revista da Associacao Medica Brasileira. 2019;65(1):43-50. | Study Design
2 | Aguas-Ayesa M, Yarnoz-Esquiroz P, Olazaran L, et al. Evaluation of Dietary and Alcohol Drinking Patterns in Patients with Excess Body Weight in a Spanish Cohort: Impact on Cardiometabolic Risk Factors. Nutrients. Nov 17 2023;15(22)doi:10.3390/nu15224824 | Study Design
3 | Alae-Carew C, Scheelbeek P, Carrillo-Larco RM, Bernabé-Ortiz A, Checkley W, Miranda JJ. Analysis of dietary patterns and cross-sectional and longitudinal associations with hypertension, high BMI and type 2 diabetes in Peru. Public Health Nutr. Apr 2020;23(6):1009-1019. | Intervention/Exposure
4 | Alves-Santos NH, Eshriqui I, Franco-Sena AB, et al. Dietary intake variations from pre-conception to gestational period according to the degree of industrial processing: A Brazilian cohort. Appetite. Oct 1 2016;105:164-71. | Outcome
5 | Ambrosini GL, Oddy WH, Robinson M, et al. Adolescent dietary patterns are associated with lifestyle and family psycho-social factors. Public Health Nutr. Oct 2009;12(10):1807-15. | Study Design, Intervention/Exposure
6 | Appannah G, Pot GK, Oddy WH, Jebb SA, Ambrosini GL. Determinants of a dietary pattern linked with greater metabolic risk and its tracking during adolescence. J Hum Nutr Diet. Apr 2018;31(2):218-227. | Intervention/Exposure, Outcome
7 | Araujo CFDS, Mello JVC, Duque AP, et al. Falta de asociación del fenotipo metabólico con el consumo de alimentos por grado de procesamiento de alimentos: resultados del Estudio de la Salud de los Trabajadores (ESAT). Article in Press. Lack of association between metabolic phenotype and food consumption by degree of food processing: results from the Study of Workers’ Health (ESAT). 2022;doi:10.20960/nh.04242 | Study Design
8 | Baird J, Poole J, Robinson S, et al. Milk feeding and dietary patterns predict weight and fat gains in infancy. Paediatr Perinat Epidemiol. Nov 2008;22(6):575-86. | Intervention/Exposure
9 | Barreto J, Assis AMO, e Santana MLP, Pitangueira JCD, Cunha CM, Costa PRF. Influence of sugar consumption from foods with different degrees of processing on anthropometric indicators of children and adolescents after 18 months of follow-up. Br J Nutr. Feb 3 2022:1-11. | Intervention/Exposure
10 | Becerra-Tomás N, Babio N, Martínez-González M, et al. Replacing red meat and processed red meat for white meat, fish, legumes or eggs is associated with lower risk of incidence of metabolic syndrome. Clin Nutr. Dec 2016;35(6):1442-1449. | Intervention/Exposure
11 | Bell LK, Golley RK, Daniels L, Magarey AM. Dietary patterns of Australian children aged 14 and 24 months, and associations with sociodemographic factors and adiposity. Eur J Clin Nutr. Jun 2013;67(6):638-45. | Study Design, Intervention/Exposure
12 | Bielemann RM, Motta JV, Minten GC, Horta BL, Gigante DP. Consumption of ultra-processed foods and their impact on the diet of young adults. Rev Saude Publica. 2015;49:28. | Study Design, Outcome
13 | Bonaccio M, Costanzo S, Ruggiero E, et al. Changes in ultra-processed food consumption during the first Italian lockdown following the COVID-19 pandemic and major correlates: results from two population-based cohorts. Public Health Nutr. Aug 2021;24(12):3905-3915. | Study Design
14 | Borloz S, Bucher Della Torre S, Collet TH, Jotterand Chaparro C. Consumption of Ultraprocessed Foods in a Sample of Adolescents With Obesity and Its Association With the Food Educational Style of Their Parent: Observational Study. JMIR Pediatr Parent. Nov 15 2021;4(4):e28608. | Study Design, Outcome
15 | Brown L, Rose K, Campbell A. Healthy plant-based diets and their short-term effects on weight loss, nutrient intake and serum cholesterol levels. Nutr Bull. Jun 2022;47(2):199-207. | Study Design, Duration, Size of study groups
16 | Bull CJ, Northstone K. Childhood dietary patterns and cardiovascular risk factors in adolescence: results from the Avon Longitudinal Study of Parents and Children (ALSPAC) cohort. Public Health Nutr. Dec 2016;19(18):3369-3377. | Intervention/Exposure
17 | Byker Shanks C, Vanderwood K, Grocke M, et al. The UnProcessed Pantry Project (UP3): A Community-Based Intervention Aimed to Reduce Ultra-Processed Food Intake Among Food Pantry Clients. Fam Community Health. Jan-Mar 01 2022;45(1):23-33. | Intervention/Exposure
18 | Canfi A, Gepner Y, Schwarzfuchs D, et al. Effect of changes in the intake of weight of specific food groups on successful body weight loss during a multi-dietary strategy intervention trial. J Am Coll Nutr. Dec 2011;30(6):491-501. | Intervention/Exposure
19 | Canhada SL, Vigo, Levy, et al. Association between ultra-processed food consumption and the incidence of type 2 diabetes: the ELSA-Brasil cohort. Article. Diabetology and Metabolic Syndrome. 2023;15(1)doi:10.1186/s13098-023-01162-2 | Outcome
20 | Casas R. Moving towards a Healthier Dietary Pattern Free of Ultra-Processed Foods. Article. Nutrients. 2022;14(1) | Study Design, Publication status
21 | Celis-Morales C, Livingstone KM, Affleck A, et al. Correlates of overall and central obesity in adults from seven European countries: findings from the Food4Me Study. Eur J Clin Nutr. Feb 2018;72(2):207-219. | Intervention/Exposure
22 | Chen F, Huang K, Long Q, et al. Comparative dietary effectiveness of a modified government-recommended diet with avoidance of ultraprocessed foods on weight and metabolic management in children and adolescents: An open-label, randomized study. Asia Pac J Clin Nutr. 2022;31(2):282-293. | Intervention/Exposure
23 | Cho Y, Ryu S, Kim R, Shin MJ, Oh H. Ultra-processed Food Intake and Risk of Type 2 Diabetes in Korean Adults. J Nutr. Jan 2024;154(1):243-251. doi:10.1016/j.tjnut.2023.11.021 | Outcome
24 | Colón-Ramos U, Racette SB, Ganiban J, et al. Association between dietary patterns during pregnancy and birth size measures in a diverse population in Southern US. Nutrients. Feb 16 2015;7(2):1318-32. | Intervention/Exposure
25 | Cornwell B, Villamor E, Mora-Plazas M, Marin C, Monteiro CA, Baylin A. Processed and ultra-processed foods are associated with lowerquality nutrient profiles in children from Colombia. Public Health Nutr. Jan 2018;21(1):142-147. | Study Design, Outcome
26 | Cortes C, Brandao JM, Cunha DB, Paravidino VB, Sichieri R. Blood pressure variation and ultra-processed food consumption in children with obesity. Eur J Pediatr. Sep 2023;182(9):4077-4085. doi:10.1007/s00431-023-05076-z | Outcome
27 | Courie R, Gaillard M, Lainas P, et al. Weight outcome after 2 years of a diet that excludes six processed foods: exploratory study of the “1,2,3 diet” in a moderately obese population. Diabetes Metab Syndr Obes. 2018;11:345-355. | Study Design, Intervention/Exposure
28 | Cummings JR, Faith MS, Lipsky LM, Liu A, Mooney JT, Nansel TR. Prospective relations of maternal reward-related eating, pregnancy ultraprocessed food intake and weight indicators, and feeding mode with infant appetitive traits. Int J Behav Nutr Phys Act. Aug 3 2022;19(1):100. | Intervention/Exposure, Outcome
29 | da Silva A, Brum Felício M, Caldas APS, et al. Ultra-processed foods consumption is associated with cardiovascular disease and cardiometabolic risk factors in Brazilians with established cardiovascular events. Int J Food Sci Nutr. Dec 2021;72(8):1128-1137. | Study Design
30 | da Silva CL, Sousa AG, Borges LPSL, Costa THM. Usual consumption of ultra-processed foods and its association with sex, age, physical activity, and body mass index in adults living in Brasília city, Brazil. Article. Revista Brasileira de Epidemiologia. 2021;24 | Study Design
31 | Dalrymple KV, Flynn AC, Seed PT, et al. Associations between dietary patterns, eating behaviours, and body composition and adiposity in 3year-old children of mothers with obesity. Pediatr Obes. May 2020;15(5):e12608. | Intervention/Exposure
32 | Dalrymple KV, Flynn AC, Seed PT, et al. Modifiable early life exposures associated with adiposity and obesity in 3-year old children born to mothers with obesity. Pediatr Obes. Nov 2021;16(11):e12801. | Intervention/Exposure
33 | Dalrymple KV, Vogel C, Flynn AC, et al. Longitudinal dietary trajectories from pregnancy to 3 years post delivery in women with obesity: relationships with adiposity. Obesity (Silver Spring). Apr 2023;31(4):1159-1169. doi:10.1002/oby.23706 | Intervention/Exposure
34 | de Bona Coradi F, Anele CR, Goldani MZ, Silva CH, Bernardi JR. Maternal diet quality and associations with body composition and diet quality of preschool children: A longitudinal study. 18(5) | Intervention/Exposure, Outcome
35 | de Melo JMM, Dourado B, e Menezes RCE, Longo-Silva G, Silveira JAC. Early onset of overweight among children from low-income families: The role of exclusive breastfeeding and maternal intake of ultra-processed food. Pediatr Obes. Dec 2021;16(12):e12825. | Intervention/Exposure, Outcome
36 | de Paula Mancilha T, Massarani FA, Vieira F, Donangelo CM, Koury JC. Birth weight, skeletal maturity and dietary patterns are associated with body composition compartments differently in male and female physically active adolescents. Nutr Health. May 2 2022:2601060221096514. | Study Design
37 | Debras C, Srour B, Chazelas E, et al. Ultra-processed foods and health: Results from the prospective NutriNet-Santé cohort. Article. Cahiers de Nutrition et de Dietetique. 2022;57(3):222-234. | Study Design, Publication language
38 | Delisle HF, Vioque J, Gil A. Dietary patterns and quality in West-African immigrants in Madrid. Nutr J. Jan 23 2009;8:3. | Study Design, Intervention/Exposure
39 | Detopoulou P, Dedes V, Pylarinou I, Syka D, Tzirogiannis K, Panoutsopoulos GI. Dietary acid load is associated with waist circumference in university students with low adherence to the Mediterranean diet: The potential role of ultra-processed foods. Article. Clinical Nutrition ESPEN. 2023;56:43-51. doi:10.1016/j.clnesp.2023.05.005 | Study Design, Intervention/Exposure, Outcome
40 | Diethelm K, Günther AL, Schulze MB, Standl M, Heinrich J, Buyken AE. Prospective relevance of dietary patterns at the beginning and during the course of primary school to the development of body composition. Br J Nutr. Apr 28 2014;111(8):1488-98. | Intervention/Exposure
41 | Drake I, Sonestedt E, Ericson U, Wallström P, Orho-Melander M. A Western dietary pattern is prospectively associated with cardio-metabolic traits and incidence of the metabolic syndrome. Br J Nutr. May 2018;119(10):1168-1176. | Intervention/Exposure
42 | Drehmer M, Odegaard AO, Schmidt MI, et al. Brazilian dietary patterns and the dietary approaches to stop hypertension (DASH) dietrelationship with metabolic syndrome and newly diagnosed diabetes in the ELSA-Brasil study. Article. Diabetology and Metabolic Syndrome. 2017;9(1) | Study Design, Intervention/Exposure
43 | Dugee O, Khor GL, Lye MS, et al. Association of major dietary patterns with obesity risk among Mongolian men and women. Asia Pac J Clin Nutr. 2009;18(3):433-40. | Study Design
44 | Durán-Agüero S, Valdés-Badilla P, Valladares M, et al. Consumption of ultra-processed food and its association with obesity in Chilean university students: A multi-center study. J Am Coll Health. Sep 1 2021:1-7. | Study Design, Intervention/Exposure
45 | Duran-Aguero S, Valdes-Badilla P, Valladares M, et al. Consumption of ultra-processed food and its association with obesity in Chilean university students: A multi-center studyUltra-processed food and obesity in Chilean university students. J Am Coll Health. Nov 2023;71(8):2356-2362. doi:10.1080/07448481.2021.1967960 | Study Design
46 | Elfassy T, Juul F, Mesa RA, Palaniappan L, Srinivasan M, Yi SS. Associations Between Ultra-processed Food Consumption and Cardiometabolic Health Among Older US Adults: Comparing Older Asian Americans to Older Adults From Other Major Race-Ethnic Groups. Res Aging. Apr 2024;46(3-4):228-240. doi:10.1177/01640275231222928 | Study Design
47 | Fangupo LJ, Haszard JJ, Taylor BJ, Gray AR, Lawrence JA, Taylor RW. Ultra-Processed Food Intake and Associations With Demographic Factors in Young New Zealand Children. J Acad Nutr Diet. Feb 2021;121(2):305-313. | Intervention/Exposure, Outcome
48 | Fazzino TL, Dorling JL, Apolzan JW, Martin CK. Meal composition during an ad libitum buffet meal and longitudinal predictions of weight and percent body fat change: The role of hyper-palatable, energy dense, and ultra-processed foods. Appetite. Dec 1 2021;167:105592. | Intervention/Exposure, Duration
49 | Filgueiras AR, Pires de Almeida VB, Koch Nogueira PC, et al. Exploring the consumption of ultra-processed foods and its association with food addiction in overweight children. Appetite. Apr 1 2019;135:137-145. | Study Design
50 | Fossee E, Zamora AN, Peterson KE, et al. Prenatal dietary patterns in relation to adolescent offspring adiposity and adipokines in a Mexico City cohort. J Dev Orig Health Dis. Jun 2023;14(3):371-380. doi:10.1017/S2040174422000678 | Intervention/Exposure, Outcome
51 | Fraga A, Bastos MP, Theme-Filha MM. Increased consumption of ultra-processed foods during pregnancy is associated with sociodemographic, behavioral, and obstetric factors: A cohort study. Nutr Res. Jan 2024;121:28-38. doi:10.1016/j.nutres.2023.10.006 | Outcome
52 | Gadelha P, e Arruda IKG, Coelho PBP, Queiroz PMA, Maio R, Silva Diniz A. Consumption of ultraprocessed foods, nutritional status, and dyslipidemia in schoolchildren: a cohort study. Eur J Clin Nutr. Aug 2019;73(8):1194-1199. | Study Design, Outcome
53 | Gete DG, Waller M, Mishra GD. Prepregnancy dietary patterns and risk of preterm birth and low birth weight: findings from the Australian Longitudinal Study on Women’s Health. Am J Clin Nutr. May 1 2020;111(5):1048-1058. | Intervention/Exposure
54 | Giacomello L, Bordignon S, Salm D, et al. Effects of the application of a food processing-based classification system in obese women: A randomized controlled pilot study. Article in Press. Nutrition and health. 2023:2601060231153947. doi:10.1177/02601060231153947 | Intervention/Exposure, Duration, Size of study groups
55 | Gibney MJ. Ultra-processed foods in public health nutrition: the unanswered questions. Journal n/a; Year n/a | Study Design, Publication status
56 | Gibney MJ. Ultra-Processed Foods: Definitions and Policy Issues. Curr Dev Nutr. Feb 2019;3(2):nzy077. | Study Design
57 | Gomes CB, Malta MB, Benício MHD, Carvalhaes M. Consumption of ultra-processed foods in the third gestational trimester and increased weight gain: a Brazilian cohort study. Public Health Nutr. Aug 2021;24(11):3304-3312. | Outcome
58 | Gómez-Donoso C, Martínez-González M, Martínez JA, Sayón-Orea C, e la Fuente-Arrillaga C, Bes-Rastrollo M. Adherence to dietary guidelines for the Spanish population and risk of overweight/obesity in the SUN cohort. PLoS One. 2019;14(12):e0226565. | Intervention/Exposure
59 | Gómez-Donoso C, Martínez-González MA, Gea A, Murphy KJ, Parletta N, Bes-Rastrollo M. A food-based score and incidence of overweight/obesity: The Dietary Obesity-Prevention Score (DOS). Clin Nutr. Dec 2019;38(6):2607-2615. | Intervention/Exposure, Overlapping data
60 | Grams L, Nelius AK, Pastor GG, et al. Comparison of Adherence to Mediterranean Diet between Spanish and German School-Children and Influence of Gender, Overweight, and Physical Activity. Nutrients. 2022;14(21) | Study Design
61 | Grech A, Rangan A, Allman-Farinelli M, Simpson SJ, Gill T, Raubenheimer D. A Comparison of the Australian Dietary Guidelines to the NOVA Classification System in Classifying Foods to Predict Energy Intakes and Body Mass Index. Nutrients. Sep 23 2022;14(19) | Study Design
62 | Gyimah EA, Nicholas JL, Waters WF, et al. Ultra-processed foods in a rural Ecuadorian community: associations with child anthropometry and bone maturation. Br J Nutr. Nov 14 2023;130(9):1609-1624. doi:10.1017/S0007114523000624 | Study Design
63 | H. Al Wattar B D, J P, A B, et al. Mediterranean-style diet in pregnant women with metabolic risk factors (ESTEEM): A pragmatic multicentre randomised trial. PLoS Med. Jul 2019;16(7):e1002857. | Intervention/Exposure
64 | Halkjaer J, Tjønneland A, Overvad K, Sørensen TI. Dietary predictors of 5-year changes in waist circumference. J Am Diet Assoc. Aug 2009;109(8):1356-66. | Intervention/Exposure
65 | Hall KD, Ayuketah A, Brychta R, et al. Ultra-Processed Diets Cause Excess Calorie Intake and Weight Gain: An Inpatient Randomized Controlled Trial of Ad Libitum Food Intake. Cell Metab. Jul 2 2019;30(1):67-77.e3. | Duration
66 | Handakas E, Chang K, Khandpur N, et al. Metabolic profiles of ultra-processed food consumption and their role in obesity risk in British children. Clin Nutr. Nov 2022;41(11):2537-2548. | Intervention/Exposure, Outcome
67 | Heidemann C, Scheidt-Nave C, Richter A, Mensink GB. Dietary patterns are associated with cardiometabolic risk factors in a representative study population of German adults. Br J Nutr. Oct 2011;106(8):1253-62. | Study Design
68 | Hinnouho GM, Ferguson EL, MacDougall A, et al. High consumption of unhealthy commercial foods and beverages tracks across the complementary feeding period in rural/peri-urban Cambodia. Matern Child Nutr. Apr 2023;19(2):e13485. doi:10.1111/mcn.13485 | Intervention/Exposure, Country
69 | Hou M, Qiu C. Ultra-Processed Food as Mediator of the Association between Birthweight and Childhood Body Weight Outcomes: A Retrospective Cohort Study. Nutrients. Oct 2023;15(19)doi:ARTN 4178 | Study Design, Outcome
70 | Hu T, Jacobs DR, Jr L, N. I C, G. J L, M. N N-S. Higher Diet Quality in Adolescence and Dietary Improvements Are Related to Less Weight Gain During the Transition From Adolescence to Adulthood. J Pediatr. Nov 2016;178:188-193.e3. | Intervention/Exposure
71 | Jardí C, Aparicio E, Bedmar C, et al. Food Consumption during Pregnancy and Post-Partum. ECLIPSES Study. Nutrients. Oct 14 2019;11(10) | Intervention/Exposure
72 | Jayasinghe SN, Breier BH, McNaughton SA, et al. Dietary Patterns in New Zealand Women: Evaluating Differences in Body Composition and Metabolic Biomarkers. Nutrients. Jul 18 2019;11(7) | Study Design, Intervention/Exposure
73 | Joseph P, Franks A, Jaime-Lara R, et al. No significant taste sensitivity or preference differences following AD libitum consumption of ultraprocessed and unprocessed diets. Journal article; Conference proceeding. Chemical senses. 2020;45:794-795. | Duration
74 | Juul F, Hemmingsson E. Trends in consumption of ultra-processed foods and obesity in Sweden between 1960 and 2010. Public Health Nutr. Dec 2015;18(17):3096-107. | Study Design
75 | Juul F, Lin Y, Deierlein AL, Vaidean G, Parekh N. Trends in food consumption by degree of processing and diet quality over 17 years: results from the Framingham Offspring Study. Br J Nutr. Dec 28 2021;126(12):1861-1871. | Outcome
76 | Kim Y, Keogh JB, Clifton PM. Differential Effects of Red Meat/Refined Grain Diet and Dairy/Chicken/Nuts/Whole Grain Diet on Glucose, Insulin and Triglyceride in a Randomized Crossover Study. Nutrients. Oct 30 2016;8(11) | Intervention/Exposure, Duration
77 | Kim Y, Keogh JB, Clifton PM. Consumption of red and processed meat and refined grains for 4weeks decreases insulin sensitivity in insulinresistant adults: A randomized crossover study. Metabolism. Mar 2017;68:173-183. | Intervention/Exposure
78 | Kim Y, Keogh JB, Clifton PM. Effects of Two Different Dietary Patterns on Inflammatory Markers, Advanced Glycation End Products and Lipids in Subjects without Type 2 Diabetes: A Randomised Crossover Study. Nutrients. Mar 29 2017;9(4) | Intervention/Exposure
79 | Konieczna J, Romaguera D, Pereira V, et al. Longitudinal association of changes in diet with changes in body weight and waist circumference in subjects at high cardiovascular risk: the PREDIMED trial. Int J Behav Nutr Phys Act. Dec 27 2019;16(1):139. | Intervention/Exposure
80 | Kostecka M, Bojanowska M, Kostecka J, Ciołek A. An analysis of dietary patterns and body composition parameters in the Polish population. Rocz Panstw Zakl Hig. 2021;72(1):55-66. | Study Design
81 | Kozioł-Kozakowska A, Kozłowska M, Jagielski P. Assessment of diet quality, nutrient intake, and dietary behaviours in obese children compared to healthy children. Pediatr Endocrinol Diabetes Metab. 2020;26(1):27-38. Ocena jakości diety, spożycia składników odżywczych i zachowań żywieniowych u dzieci otyłych w porównaniu z dziećmi zdrowymi. | Study Design
82 | Kurniawan AL, Hsu CY, Lee HA, et al. Comparing two methods for deriving dietary patterns associated with risk of metabolic syndrome among middle-aged and elderly Taiwanese adults with impaired kidney function. Article. BMC medical research methodology. 2020;20(1):255. | Study Design, Intervention/Exposure
83 | Lane MM, Lotfaliany M, Hodge AM, et al. High ultra-processed food consumption is associated with elevated psychological distress as an indicator of depression in adults from the Melbourne Collaborative Cohort Study. J Affect Disorders. Aug 15 2023;335:57-66. doi:10.1016/j.jad.2023.04.124 | Outcome
84 | Lasschuijt M, Camps G, Mars M, Siebelink E, de Graaf K, Bolhuis D. Speed limits: the effects of industrial food processing and food texture on daily energy intake and eating behaviour in healthy adults. Eur J Nutr. Oct 2023;62(7):2949-2962. doi:10.1007/s00394-023-03202-z | Duration
85 | Latorre-Millán M, Rupérez AI, González-Gil EM, et al. Dietary Patterns and Their Association with Body Composition and Cardiometabolic Markers in Children and Adolescents: Genobox Cohort. Nutrients. Nov 8 2020;12(11) | Study Design, Intervention/Exposure
86 | Lauria F, Dello Russo M, Formisano A, et al. Ultra-processed foods consumption and diet quality of European children, adolescents and adults: Results from the I.Family study. Article. Nutrition, Metabolism and Cardiovascular Diseases. 2021;31(11):3031-3043. | Study Design, Outcome
87 | Leblanc V, Hudon AM, Royer MM, et al. Differences between men and women in dietary intakes and metabolic profile in response to a 12week nutritional intervention promoting the Mediterranean diet. J Nutr Sci. 2015;4:e13. | Intervention/Exposure
88 | León-Muñoz LM, García-Esquinas E, López-García E, Banegas JR, Rodríguez-Artalejo F. Major dietary patterns and risk of frailty in older adults: a prospective cohort study. BMC Med. Jan 20 2015;13:11. | Intervention/Exposure, Outcome
89 | Lim SX, Cox V, Rodrigues N, et al. Evaluation of Preconception Dietary Patterns in Women Enrolled in a Multisite Study. Curr Dev Nutr. Jul 2022;6(7):nzac106. doi:10.1093/cdn/nzac106 | Study Design, Intervention/Exposure
90 | Lima BB, Lopes ACS, ior LAA, Lopes MS, Freitas PP, Menezes MC. Effectiveness of the promoting adequate and healthy eating (PAAS) program in primary care: community randomized controlled trial. Article in Press. Journal of Public Health (Germany). 2023;doi:10.1007/s10389-023-02131-9 | Intervention/Exposure, Outcome
91 | Lioret S, Betoko A, Forhan A, et al. Dietary patterns track from infancy to preschool age: cross-sectional and longitudinal perspectives. Article. J Nutr. Apr 2015;145(4):775-82. doi:10.3945/jn.114.201988 | Outcome
92 | Lourenco BH, Castro MC, de Morais Sato P, et al. Exposure to ultra-processed foods during pregnancy and ultrasound fetal growth parameters. Br J Nutr. Dec 28 2023;130(12):2136-2145. doi:10.1017/S0007114523001204 | Outcome
93 | Lourenço BH, Castro MC, Sato PM, et al. Exposure to ultra-processed foods during pregnancy and ultrasound foetal growth parameters. | Outcome
94 | Louzada ML, Steele EM, Rezende LFM, Levy RB, Monteiro CA. Changes in Obesity Prevalence Attributable to Ultra-Processed Food Consumption in Brazil Between 2002 and 2009. Int J Public Health. 2022;67:1604103. | Study Design
95 | Luque V, Escribano J, Closa-Monasterolo R, et al. Unhealthy Dietary Patterns Established in Infancy Track to Mid-Childhood: The EU Childhood Obesity Project. J Nutr. May 1 2018;148(5):752-759. | Intervention/Exposure
96 | Machado PP, Steele EM, Levy RB, et al. Ultra-processed food consumption and obesity in the Australian adult population. Nutr Diabetes. Dec 5 2020;10(1):39. | Study Design
97 | Madalosso MM, Martins NNF, Medeiros BM, et al. Consumption of ultra-processed foods and cardiometabolic risk factors in Brazilian adolescents: results from ERICA. Eur J Clin Nutr. Nov 2023;77(11):1084-1092. doi:10.1038/s41430-023-01329-0 | Study Design
98 | Magalhães E, e Oliveira BR, Rudakoff LCS, et al. Sex-Dependent Effects of the Intake of NOVA Classified Ultra-Processed Foods on Syndrome Metabolic Components in Brazilian Adults. Nutrients. Jul 29 2022;14(15) | Size of study groups
99 | Mai TMT, Tran QC, Nambiar S, Gallegos D, Van der Pols JC. Dietary patterns and child, parental, and societal factors associated with being overweight and obesity in Vietnamese children living in Ho Chi Minh city. Article in Press. Maternal & child nutrition. 2023:e13514. doi:10.1111/mcn.13514 | Study Design, Country
100 | Martin CL, Siega-Riz AM, Sotres-Alvarez D, et al. Maternal Dietary Patterns are Associated with Lower Levels of Cardiometabolic Markers during Pregnancy. Paediatr Perinat Epidemiol. May 2016;30(3):246-55. | Intervention/Exposure
101 | Martin CL, Siega-Riz AM, Sotres-Alvarez D, et al. Maternal Dietary Patterns during Pregnancy Are Associated with Child Growth in the First 3 Years of Life. J Nutr. Nov 2016;146(11):2281-2288. | Intervention/Exposure
102 | Martinez-Perez C, San-Cristobal R, Guallar-Castillon P, et al. Use of Different Food Classification Systems to Assess the Association between Ultra-Processed Food Consumption and Cardiometabolic Health in an Elderly Population with Metabolic Syndrome (PREDIMEDPlus Cohort). Nutrients. Jul 20 2021;13(7) | Study Design
103 | Martins AP, Benicio MH. Influence of dietary intake during gestation on postpartum weight retention. Rev Saude Publica. Oct 2011;45(5):870-7. | Intervention/Exposure, Publication language
104 | Mattei J, Noel SE, Tucker KL. A meat, processed meat, and French fries dietary pattern is associated with high allostatic load in Puerto Rican older adults. J Am Diet Assoc. Oct 2011;111(10):1498-506. | Intervention/Exposure, Outcome
105 | Mertens E, Colizzi C, Peñalvo JL. Ultra-processed food consumption in adults across Europe. Eur J Nutr. Apr 2022;61(3):1521-1539. | Study Design
106 | Mertens E, Markey O, Geleijnse JM, Givens DI, Lovegrove JA. Dietary Patterns in Relation to Cardiovascular Disease Incidence and Risk Markers in a Middle-Aged British Male Population: Data from the Caerphilly Prospective Study. Nutrients. Jan 18 2017;9(1) | Intervention/Exposure, Outcome
107 | Mikeš O, Brantsæter AL, Knutsen HK, et al. Dietary patterns and birth outcomes in the ELSPAC pregnancy cohort. J Epidemiol Community Health. Jun 2022;76(6):613-619. | Intervention/Exposure, Outcome
108 | Morris TT, Northstone K. Rurality and dietary patterns: associations in a UK cohort study of 10-year-old children. Public Health Nutr. Jun 2015;18(8):1436-43. | Study Design, Outcome
109 | Moubarac JC, Martins AP, Claro RM, Levy RB, Cannon G, Monteiro CA. Consumption of ultra-processed foods and likely impact on human health. Evidence from Canada. Public Health Nutr. Dec 2013;16(12):2240-8. | Study Design, Outcome
110 | Mullen A. Ultraprocessed food and cardiometabolic disease. Article. Nature Food. 2021;2(8):554. doi:10.1038/s43016-021-00355-0 | Study Design , Publication status
111 | Muslimatun S, Wiradnyani LA. Dietary diversity, animal source food consumption and linear growth among children aged 1-5 years in Bandung, Indonesia: a longitudinal observational study. Br J Nutr. Jul 2016;116 Suppl 1:S27-35. | Intervention/Exposure, Country
112 | Nardocci M, Leclerc BS, Louzada ML, Monteiro CA, Batal M, Moubarac JC. Correction to: Consumption of ultra-processed foods and obesity in Canada. Can J Public Health. Feb 2019;110(1):15-16. | Study Design , Publication status
113 | Neri D, Steele EM, Khandpur N, et al. Ultraprocessed food consumption and dietary nutrient profiles associated with obesity: A multicountry study of children and adolescents. Obes Rev. Jan 2022;23 Suppl 1:e13387. | Study Design, Outcome
114 | Nettleton JA, Follis JL, Ngwa JS, et al. Gene × dietary pattern interactions in obesity: analysis of up to 68 317 adults of European ancestry. Hum Mol Genet. Aug 15 2015;24(16):4728-38. | Intervention/Exposure
115 | Nettleton JA, Schulze MB, Jiang R, Jenny NS, Burke GL, Jacobs DR. A priori-defined dietary patterns and markers of cardiovascular disease risk in the Multi-Ethnic Study of Atherosclerosis (MESA). Am J Clin Nutr. Jul 2008;88(1):185-94. | Study Design, Intervention/Exposure
116 | Neves AM, Madruga SW. Complementary feeding, consumption of industrialized foods and nutritional status of children under 3 years old in Pelotas, Rio Grande do Sul, Brazil, 2016: a descriptive study. Epidemiol Serv Saude. 2019;28(1):e2017507. Alimentação complementar, consumo de alimentos industrializados e estado nutricional de crianças menores de 3 anos em Pelotas, Rio Grande do Sul, Brasil, 2016: um estudo descritivo. | Study Design
117 | Newby PK, Muller D, Hallfrisch J, Qiao N, Andres R, Tucker KL. Dietary patterns and changes in body mass index and waist circumference in adults. Am J Clin Nutr. Jun 2003;77(6):1417-25. | Intervention/Exposure
118 | Ng CM, Kaur S, Koo HC, Mukhtar F, Yim HS. Experiential healthy meal preparation: A randomized-controlled trial to improve food group consumption and weight status among children. Article. Human Nutrition and Metabolism. 2022;28 | Intervention/Exposure
119 | Nogueira MB, Mazzucchetti L, Mosquera PS, Cardoso MA, Malta MB. Consumption of ultra-processed foods during the first year of life and associated factors in Cruzeiro do Sul, Brazil. Article. Ciencia e Saude Coletiva. 2022;27(2):725-736. | Outcome
120 | Northstone K, Emmett P, Rogers I. Dietary patterns in pregnancy and associations with socio-demographic and lifestyle factors. Eur J Clin Nutr. Apr 2008;62(4):471-9. | Study Design, Outcome
121 | Northstone K, Smith AD, Newby PK, Emmett PM. Longitudinal comparisons of dietary patterns derived by cluster analysis in 7- to 13-yearold children. Br J Nutr. Jun 2013;109(11):2050-8. | Study Design, Outcome
122 | O’Connor LE, Hall KD, Herrick KA, et al. Metabolomic Profiling of an Ultraprocessed Dietary Pattern in a Domiciled Randomized Controlled Crossover Feeding Trial. J Nutr. Aug 2023;153(8):2181-2192. doi:10.1016/j.tjnut.2023.06.003 | Duration
123 | Oddo VM, Maehara M, Rah JH. Overweight in Indonesia: an observational study of trends and risk factors among adults and children. BMJ Open. Sep 27 2019;9(9):e031198. | Intervention/Exposure, Country
124 | Pala V, Sieri S, Masala G, et al. Associations between dietary pattern and lifestyle, anthropometry and other health indicators in the elderly participants of the EPIC-Italy cohort. Nutr Metab Cardiovasc Dis. Apr 2006;16(3):186-201. | Intervention/Exposure
125 | Pan F, Wang ZH, Wang HJ, et al. Association between Ultra-Processed Food Consumption and Metabolic Syndrome among Adults in China-Results from the China Health and Nutrition Survey. Nutrients. Feb 2023;15(3)doi:ARTN 75210.3390/nu15030752 | Study Design
126 | Pan F, Zhang T, Mao W, Zhao F, Luan D, Li J. Ultra-Processed Food Consumption and Risk of Overweight or Obesity in Chinese Adults: Chinese Food Consumption Survey 2017-2020. Nutrients. Sep 16 2023;15(18)doi:10.3390/nu15184005 | Study Design
127 | Pang T, Alman AC, Gray HL, Basu A, Shi L, Snell-Bergeon JK. Empirical dietary inflammatory pattern and metabolic syndrome: prospective association in participants with and without type 1 diabetes mellitus in the coronary artery calcification in type 1 diabetes (CACTI) study. Nutr Res. Oct 2021;94:1-9. | Size of study groups
128 | Pang TT, Gray HL, Alman AC, et al. Ultra-processed food consumption and obesity indicators in individuals with and without type 1 diabetes mellitus: a longitudinal analysis of the prospective Coronary Artery Calcification in Type 1 Diabetes (CACTI) cohort study. Public Health Nutrition. Aug 2023;26(8):1626-1633. doi:Pii S1368980023000848 | Intervention/Exposure, Size of study groups
129 | Papagianni O, Maniati E, Pegkos A, et al. Association between functional and novel food consumption frequency and obesity anthropometric indexes, in a sample of healthy volunteers: a retro prospective study. Journal article; Conference proceeding. Obesity facts. 2021;14(SUPPL 1):174-175.doi:10.1017/S1368980023000848 | Intervention/Exposure Publication status
130 | Pereira AM, Buffarini R, Domingues MR, Barros F, Silveira MFD. Ultra-processed food consumption by children from a Pelotas Birth Cohort. Rev Saude Publica. 2022;56:79. | Study Design, Outcome
131 | Pereyra-González I, Mattei J. Combined intake of sugar-sweetened beverages and sugar-containing ultra-processed foods is associated with an increase in body mass index during early childhood. | Intervention/Exposure
132 | Perez-Escamilla R. Ultra-processed foods and the nutritional transition among infants and young children: a radiography from Brazil. Article. Alimentos ultraprocessados e a transi??o nutricional em beb?s e crian?as pequenas: uma radiografia do Brasil. 2023;39doi:10.1590/0102311XEN118123 | Study Design, Publication status
133 | Philip Karl J, Armstrong NJ, Player RA, Rood JC, Soares JW, McClung HL. The Fecal Metabolome Links Diet Composition, Foacidic positive ion conditions, chromatographicallyod Processing, and the Gut Microbiota to Gastrointestinal Health in a Randomized Trial of Adults Consuming a Processed Diet. Article. Journal of Nutrition. 2022;152(11):2343-2357. doi:10.1093/jn/nxac161 | Duration
134 | Phillips NE, Mareschal J, Schwab N, et al. The Effects of Time-Restricted Eating versus Standard Dietary Advice on Weight, Metabolic Health and the Consumption of Processed Food: a Pragmatic Randomised Controlled Trial in Community-Based Adults. Journal Article; Clinical Trial Protocol. Nutrients. 2021;13(3) | Intervention/Exposure, Duration
135 | Pinto A, Santos AC, Lopes C, Oliveira A. Dietary patterns at 7 year-old and their association with cardiometabolic health at 10 year-old. Clin Nutr. Apr 2020;39(4):1195-1202. | Intervention/Exposure
136 | Pinto A, Severo M, Oliveira A. Use of a hybrid method to derive dietary patterns in 7 years olds with explanatory ability of body mass index at age 10. Eur J Clin Nutr. Nov 2021;75(11):1598-1606. | Intervention/Exposure
137 | Poll FA, Miraglia F, D’Avila H F, Reuter CP, Mello ED. Impact of intervention on nutritional status, consumption of processed foods, and quality of life of adolescents with excess weight. J Pediatr (Rio J). Sep-Oct 2020;96(5):621-629. | Intervention/Exposure, Outcome
138 | Pou SA, Del Pilar Díaz M, De La Quintana AG, Forte CA, Aballay LR. Identification of dietary patterns in urban population of Argentina: study on diet-obesity relation in population-based prevalence study. Nutr Res Pract. Dec 2016;10(6):616-622. | Study Design, Intervention/Exposure
139 | Raspini B, Prosperi M, Guiducci L, et al. Dietary Patterns and Weight Status in Italian Preschoolers with Autism Spectrum Disorder and Typically Developing Children. Nutrients. Nov 12 2021;13(11) | Study Design, Intervention/Exposure
140 | Rauber F, Campagnolo PDB, Hoffman DJ, Vitolo MR. Consumption of ultra-processed food products and its effects on children’s lipid profiles: A longitudinal study. Article. Nutrition, Metabolism and Cardiovascular Diseases. 2015;25(1):116-122. | Outcome
141 | Rauber F, Steele EM, Costa Louzada ML, Millett C, Monteiro CA, Levy RB. Ultra-processed food consumption and indicators of obesity in the United Kingdom population (2008-2016). Article. PLoS ONE. 2020;15(5) | Study Design
142 | Razmpoosh E, Zare S, Fallahzadeh H, Safi S, Nadjarzadeh A. Effect of a low energy diet, containing a high protein, probiotic condensed yogurt, on biochemical and anthropometric measurements among women with overweight/obesity: A randomised controlled trial. Clin Nutr ESPEN. Feb 2020;35:194-200. | Intervention/Exposure, Duration
143 | Ribeiro IDC, Santos de Almeida Oliveira TLP, Santos GCJ, et al. Daily consumption of ultra-processed foods and cardiometabolic risk factors in children aged 7 to 10 years in Northeast Brazil. Article in Press. Nutrition and health. 2022:2601060221084816. | Study Design
144 | Riboldi BP, Luft VC, Bracco PA, et al. The inflammatory food index and its association with weight gain and incidence of diabetes: Longitudinal Study of Adult Health (ELSA-Brasil). Nutr Metab Cardiovasc Dis. Mar 2022;32(3):675-683. | Intervention/Exposure, Overlapping data
145 | Romaguera D, Ängquist L, Du H, et al. Food composition of the diet in relation to changes in waist circumference adjusted for body mass index. PLoS One. 2011;6(8):e23384. | Intervention/Exposure
146 | Rosignoli da Conceição A, Silva A, Marcadenti A, Bersch-Ferreira Â C, Weber B, Bressan J. Consumption of unprocessed or minimally processed foods and their association with cardiovascular events and cardiometabolic risk factors in Brazilians with established cardiovascular events. | Health Status, Study Design
147 | Ryman TK, Boyer BB, Hopkins S, et al. Associations between diet and cardiometabolic risk among Yup’ik Alaska Native people using food frequency questionnaire dietary patterns. Nutr Metab Cardiovasc Dis. Dec 2015;25(12):1140-5. | Study Design
148 | Saldanha-Gomes C, Hallimat Cissé A, Descarpentrie A, et al. Prospective associations between dietary patterns, screen and outdoor play times at 2 years and age at adiposity rebound: The EDEN mother-child cohort. Prev Med Rep. Feb 2022;25:101666. | Intervention/Exposure
149 | Salvesen L, Valen EN, Wills AK, et al. Developmental origins of health and disease knowledge is associated with diet quality in preconception young adult men and women. J Dev Orig Hlth Dis. Oct 2023;14(5):631-638. doi:10.1017/S2040174423000314 | Study Design, Intervention/Exposure, Outcome
150 | Sandoval-Insausti H, Blanco-Rojo R, Graciani A, et al. Ultra-processed Food Consumption and Incident Frailty: A Prospective Cohort Study of Older Adults. J Gerontol A Biol Sci Med Sci. May 22 2020;75(6):1126-1133. | Outcome
151 | Sandoval-Insausti H, Jiménez-Onsurbe M, Donat-Vargas C, et al. Ultra-Processed Food Consumption Is Associated with Abdominal Obesity: A Prospective Cohort Study in Older Adults. Nutrients. Aug 7 2020;12(8) | Size of study groups
152 | Santos LP, Assunção MC, Matijasevich A, Santos IS, Barros AJ. Dietary intake patterns of children aged 6 years and their association with socioeconomic and demographic characteristics, early feeding practices and body mass index. Article. BMC public health. 2016;16(1):1055. | Study Design, Intervention/Exposure
153 | Sartorelli DS, Crivellenti LC, Baroni NF, et al. Effectiveness of a minimally processed food-based nutritional counselling intervention on weight gain in overweight pregnant women: a randomized controlled trial. Eur J Nutr. Sep 10 2022:1-12. | Intervention/Exposure
154 | Schnabel L, Buscail C, Sabate JM, et al. Association Between Ultra-Processed Food Consumption and Functional Gastrointestinal Disorders: Results From the French NutriNet-Santé Cohort. Am J Gastroenterol. Aug 2018;113(8):1217-1228. | Study Design, Outcome
155 | Schneider BC, Dumith Sde C, Lopes C, Severo M, Assunção MC. How Do Tracking and Changes in Dietary Pattern during Adolescence Relate to the Amount of Body Fat in Early Adulthood? PLoS One. 2016;11(2):e0149299. | Intervention/Exposure
156 | Schulz M, Nöthlings U, Hoffmann K, Bergmann MM, Boeing H. Identification of a food pattern characterized by high-fiber and low-fat food choices associated with low prospective weight change in the EPIC-Potsdam cohort. J Nutr. May 2005;135(5):1183-9. | Intervention/Exposure
157 | Schulze MB, Fung TT, Manson JE, Willett WC, Hu FB. Dietary patterns and changes in body weight in women. Obesity (Silver Spring). Aug 2006;14(8):1444-53. | Intervention/Exposure
158 | Sciarrillo CM, Guo J, Hengist A, Darcey VL, Hall KD. Diet order affects energy balance in randomized crossover feeding studies that vary in macronutrients but not ultra-processing. | Duration
159 | Seale E, Greene-Finestone LS, e Groh M. Examining the diversity of ultra-processed food consumption and associated factors in Canadian adults. Appl Physiol Nutr Metab. Aug 2020;45(8):857-864. | Study Design
160 | Shah RV, Murthy VL, Allison MA, et al. Diet and adipose tissue distributions: The Multi-Ethnic Study of Atherosclerosis. Nutr Metab Cardiovasc Dis. Mar 2016;26(3):185-93. | Intervention/Exposure
161 | Sherafat-Kazemzadeh R, Egtesadi S, Mirmiran P, et al. Dietary patterns by reduced rank regression predicting changes in obesity indices in a cohort study: Tehran Lipid and Glucose Study. Asia Pac J Clin Nutr. 2010;19(1):22-32. | Intervention/Exposure
162 | Shim JS, Ha KH, Kim DJ, Kim HC. Ultra-Processed Food Consumption and Obesity in Korean Adults. Diabetes Metab J. Jul 2023;47(4):547-558. doi:10.4093/dmj.2022.0026 | Study Design
163 | Shim JS, Ha KH, Kim DJ, Kim HC. Diet quality partially mediates the association between ultraprocessed food consumption and adiposity indicators. Article in Press. Obesity (Silver Spring, Md). 2023;doi:10.1002/oby.23853 | Study Design
164 | Shim SY, Kim HC, Shim JS. Consumption of Ultra-Processed Food and Blood Pressure in Korean Adults. Korean Circ J. Jan 2022;52(1):6070. | Study Design
165 | Silva Dos Santos F, Costa Mintem G, e Oliveira IO, et al. Consumption of ultra-processed foods and interleukin-6 in two cohorts from high- and middle-income countries. Br J Nutr. Feb 21 2022:1-28.doi:10.1017/S0007114522000551 | Outcome
166 | Silva CFM, Saunders C, Peres W, et al. Effect of ultra-processed foods consumption on glycemic control and gestational weight gain in pregnant with pregestational diabetes mellitus using carbohydrate counting. PeerJ. 2021;9:e10514. | Health Status
167 | Smit AJP, Hojeij B, Rousian M, et al. A high periconceptional maternal ultra-processed food consumption impairs embryonic growth: The Rotterdam periconceptional cohort. Clin Nutr. Aug 2022;41(8):1667-1675. | Outcome
168 | Smith AD, Emmett PM, Newby PK, Northstone K. Dietary patterns and changes in body composition in children between 9 and 11 years. Food Nutr Res. 2014;58 | Intervention/Exposure
169 | Steffen LM, Van Horn L, Daviglus ML, et al. A modified Mediterranean diet score is associated with a lower risk of incident metabolic syndrome over 25 years among young adults: the CARDIA (Coronary Artery Risk Development in Young Adults) study. Br J Nutr. Nov 28 2014;112(10):1654-61. | Intervention/Exposure
170 | Sterling S, Bertrand B, Judd S, Carson TL, Chandler-Laney P, Baskin ML. Longitudinal Analysis of Nut-Inclusive Diets and Body Mass Index Among Overweight and Obese African American Women Living in Rural Alabama and Mississippi, 2011-2013. Prev Chronic Dis. Sep 21 2017;14:E82. | Intervention/Exposure
171 | Sterling S, Judd S, Bertrand B, Carson TL, Chandler-Laney P, Baskin ML. Dietary Patterns Among Overweight and Obese African-American Women Living in the Rural South. J Racial Ethn Health Disparities. Feb 2018;5(1):141-150. | Study Design, Intervention/Exposure
172 | Strathearn L, Kaçar HK, Avery A. Changes in dietary patterns when females engage in a weight management programme and their ability to meet Scientific Advisory Committee on Nutrition’s fibre and sugar recommendations. Public Health Nutr. Aug 2020;23(12):2189-2198. | Study Design, Intervention/ExposureDuration
173 | Teixeira JA, Hoffman DJ, Castro TG, et al. Pre-pregnancy dietary pattern is associated with newborn size: results from ProcriAr study. Br J Nutr. Sep 28 2021;126(6):903-912. | Intervention/Exposure, Outcome
174 | Thorning TK, Raziani F, Bendsen NT, Astrup A, Tholstrup T, Raben A. Diets with high-fat cheese, high-fat meat, or carbohydrate on cardiovascular risk markers in overweight postmenopausal women: a randomized crossover trial. Am J Clin Nutr. Sep 2015;102(3):573-81. | Intervention/Exposure, Duration Size of study groups
175 | Ushula TW, Mamun A, Darssan D, et al. Dietary patterns and the risks of metabolic syndrome and insulin resistance among young adults: Evidence from a longitudinal study. Clin Nutr. Jul 2022;41(7):1523-1531. | Intervention/Exposure, Outcome
176 | Valmorbida JL, Baratto PS, Leffa PS, Sangalli CN, Silva JA, Vitolo MR. Consumption of ultraprocessed food is associated with higher blood pressure among 6-year-old children from southern Brazil. Nutrition Research. Aug 2023;116:60-68. doi:10.1016/j.nutres.2023.05.012 | Outcome
177 | Vandevijvere S, De Ridder K, Fiolet T, Bel S, Tafforeau J. Consumption of ultra-processed food products and diet quality among children, adolescents and adults in Belgium. Article. European Journal of Nutrition. 2019;58(8):3267-3278. | Study Design, Outcome
178 | Vang A, Singh PN, Lee JW, Haddad EH, Brinegar CH. Meats, processed meats, obesity, weight gain and occurrence of diabetes among adults: findings from Adventist Health Studies. Ann Nutr Metab. 2008;52(2):96-104. | Intervention/Exposure, Outcome
179 | Veum VL, Laupsa-Borge J, Eng Ø, et al. Visceral adiposity and metabolic syndrome after very high-fat and low-fat isocaloric diets: a randomized controlled trial. Journal Article; Clinical Trial Protocol. American journal of clinical nutrition. 2017;105(1):85-99. | Intervention/Exposure
180 | Wang Y, Lindemann SR, Cross TL, Tang M, Clark CM, Campbell WW. Effects of Adding Lean Red Meat to a U.S.-Style Healthy Vegetarian Dietary Pattern on Gut Microbiota and Cardiovascular Risk Factors in Young Adults: a Crossover Randomized Controlled Trial. J Nutr. May 2023;153(5):1439-1452. doi:10.1016/j.tjnut.2023.03.013 | Intervention/Exposure Duration Size of study groups
181 | Wang Y, Dai Y, Tian T, et al. The effects of dietary pattern on metabolic syndrome in jiangsu province of china: Based on a nutrition and diet investigation project in Jiangsu province. Article. Nutrients. 2021;13(12) | Study Design
182 | Wang Y, Wang K, Du M, et al. Maternal consumption of ultra-processed foods and subsequent risk of offspring overweight or obesity: Results from three prospective cohort studies. Article in Press. The BMJ. 2022;doi:10.1136/bmj-2022-071767 | Intervention/Exposure, Outcome
183 | Weigel MM, Armijos RX. The Ecuadorian School Food Environment: Association With Healthy and Unhealthy Food and Beverage Consumption and BMI. Food Nutr Bull. Dec 2022;43(4):439-464. | Study Design
184 | Wen LM, Simpson JM, Rissel C, Baur LA. Maternal “junk food” diet during pregnancy as a predictor of high birthweight: findings from the healthy beginnings trial. Birth. Mar 2013;40(1):46-51. | Intervention/Exposure, Outcome
185 | Winkvist A, Klingberg S, Nilsson LM, et al. Longitudinal 10-year changes in dietary intake and associations with cardio-metabolic risk factors in the Northern Sweden Health and Disease Study. Nutr J. Mar 28 2017;16(1):20. | Intervention/Exposure
186 | Woolhead C, Walsh MC, Gibney MJ, et al. Dietary patterns in Europe: the Food4Me proof of principle study. Journal article; Conference proceeding. Proceedings of the Nutrition Society. 2015;74(OCE4) | Publication status
187 | Wosje KS, Khoury PR, Claytor RP, et al. Dietary patterns associated with fat and bone mass in young children. Am J Clin Nutr. Aug 2010;92(2):294-303. | Intervention/Exposure
188 | Wrottesley SV, Prioreschi A, Kehoe SH, Ward KA, Norris SA. A maternal “mixed, high sugar” dietary pattern is associated with fetal growth. Matern Child Nutr. Apr 2020;16(2):e12912. | Intervention/Exposure, Country
189 | Yong HY, Shariff ZM, Mohd Yusof BN, et al. Associations between the dietary patterns of pregnant Malaysian women and ethnicity, education, and early pregnancy waist circumference: A prospective cohort study. Nutr Res Pract. Jun 2019;13(3):230-239. | Intervention/Exposure
190 | Zhen S, Ma Y, Zhao Z, Yang X, Wen D. Dietary pattern is associated with obesity in Chinese children and adolescents: data from China Health and Nutrition Survey (CHNS). Nutr J. Jul 11 2018;17(1):68. | Intervention/Exposure, Country
191 | Zhou Y, Du S, Su C, Zhang B, Wang H, Popkin BM. The food retail revolution in China and its association with diet and health. Food Policy. Aug 1 2015;55:92-100. | Study Design, Intervention/Exposure