# Appendix 2 Literature search strategy

## Search from another systematic review

The search conducted for another review was used to conduct a manual search to identify additional articles. For the complete search documentation, refer to:

Hoelscher DM, Tobias, . Dietary Patterns and Growth, Body Composition, and Risk of Obesity: A Systematic Review U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review; 2025. 10.52570/NESR.DGAC2025.SR01

## Search for the current review

This search was first run on December 16, 2022, and then periodically run using NESR’s continuous evidence monitoring methods^*^ until January 2024.

* USDA Nutrition Evidence Systematic Review Branch. Chapter 10: Continuous Evidence Monitoring. In: USDA Nutrition Evidence Systematic Review: Methodology Manual. February 2023. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://nesr.usda.gov/methodology-overview.

### Database: PubMed

Provider: U.S. National Library of Medicine

Date(s) Searched: December 16, 2022 (initial search); December 16, 2022 -January 9, 2024 (continuous evidence monitoring)

Dates Covered: January 1, 2000 – January 9, 2024

Table A 2 Search for PubMed

Search # | Concept | String
#1 | Ultra processed foods | ((Fast Foods[MeSH] OR Food Handling[MeSH]) AND process*[tiab]) OR ((ultraprocessed[tiab] OR processed[tiab]) AND (food*[tiab] OR product*[tiab] OR “dietary pattern*”[tiab])) OR “NOVA classification”[tiab] OR “NOVA food”[tiab] OR “NOVA categor*”[tiab] OR (SIGA[tiab] AND (index[tiab] OR classification[tiab] OR algorithm[tiab])) OR Hyper palatab*”[tiab] OR “Hyperpalatab*”[tiab] OR “highly palatable”[tiab] OR “high palatability”[tiab]
#2 | Growth, body composition, and risk of obesity | “Adipose Tissue”[Mesh] OR “Body Composition”[Mesh] OR “Body Weights and Measures”[MeSH:NoExp] OR “Body Fat Distribution”[Mesh] OR “Body Mass Index"[Mesh] OR “Body Size”[Mesh] OR “Skinfold Thickness”[Mesh] OR “Waist-Hip Ratio”[Mesh] OR “Overnutrition”[Mesh] OR “Growth”[Mesh:NoExp] OR anthropometr*[tiab] OR body fat[tiab] OR fat mass[tiab] OR fat free mass[tiab] OR lean mass[tiab] OR obese[tiab] OR obesity[tiab] OR underweight[tiab] OR overweight[tiab] OR weight status[tiab] OR head circumference[tiab] OR arm circumference[tiab] OR calf circumference[tiab] OR neck circumference[tiab] OR thigh circumference[tiab] OR waist circumference[tiab] OR waist to hip ratio[tiab] OR waist hip ratio[tiab] OR body mass index[tiab] OR BMI[tiab] OR adipos*[tiab] OR body weight[tiab] OR body height[tiab] OR body size[tiab] OR body composition[tiab] OR overnutrition[tiab] OR wasting[tiab] OR healthy weight[tiab] OR skin fold[tiab] OR skin folds[tiab] OR skinfold[tiab] OR skinfolds[tiab] OR “Weight Reduction Programs”[Mesh] OR “Body-Weight Trajectory”[Mesh] OR “Weight Gain”[MeSH] OR “Weight Loss”[MeSH:NoExp] OR “Diet, Reducing”[Mesh] OR weight gain*[tiab] OR diet reduc*[tiab] OR weight cycling[tiab] OR weight decreas*[tiab] OR weight watch*[tiab] OR weight control*[tiab] OR weight retention[tiab] OR weight management[tiab] OR (weight[tiab] AND (maint*[tiab] OR reduc*[tiab] OR loss*[tiab] OR chang*[tiab])) OR “Growth Charts”[Mesh] OR growth chart*[tiab]OR stunting[tiab] OR stunted[tiab] OR weight for height[tiab] OR stature for age[tiab] OR weight for age[tiab] OR height for age[tiab] OR length for age[tiab] OR weight for length[tiab] OR failure to thrive[tiab]
#3 | | #1 AND #2
#4 | | #3 NOT (“Animals”[Mesh] NOT (“Animals”[Mesh] AND “Humans”[Mesh])); NOT (editorial[ptyp] OR comment[ptyp] OR commentary[tiab] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic review[ptyp] OR systematic review[ti] OR meta-analysis[ptyp] OR meta-analysis[ti] OR meta-analyses[ti] OR protocol[ti] OR protocols[ti] OR retracted publication[ptyp] OR retraction of publication[ptyp] OR retraction of publication[tiab] OR retraction notice[ti] OR “retracted publication”[ti] OR “Congress"[Publication Type] OR “Consensus Development Conference"[Publication Type] OR “conference abstract*”[tiab] OR “conference proceeding*”[tiab] OR “conference paper*”[tiab] OR “practice guideline“[ptyp] OR “practice guideline”[ti]); Filters applied: English, from 2000/1/1 - 3000/12/12.

### Database: Embase

Provider: Elsevier

Date(s) Searched: December 16, 2022 (initial search); December 16, 2022 -January 9, 2024 (continuous evidence monitoring)

Dates Covered: January 1, 2000 – January 9, 2024

Table A 3 Search for Embase

Search # | Concept | String
#1 | Ultra processed foods | ‘ultra-processed food’/exp OR (‘Fast Food’/exp OR ‘Food Handling’/exp AND process*:ab,ti) OR ((ultraprocessed OR processed) NEAR/3 (food* OR product* OR ‘dietary pattern*’)):ab,ti OR ‘NOVA classification’:ab,ti OR ‘NOVA food’:ab,ti OR ‘NOVA categor*’:ab,ti OR (‘SIGA’ NEAR (index OR classification OR algorithm)):ab,ti OR ‘Hyper palatab*’:ab,ti OR ‘Hyperpalatab*’:ab,ti OR ‘highly palatable’:ab,ti OR ‘high palatability’:ab,ti
#2 | Growth, body composition, and risk of obesity | ‘adipose tissue’/exp OR ‘body composition’/exp OR ‘anthropometry’/de OR ‘body mass’/exp OR ‘anthropometric parameters’/exp OR ‘skinfold thickness’/exp OR ‘overnutrition’/exp OR ‘growth’/de OR ‘anthropometr*’:ab,ti OR ‘body fat’:ab,ti OR ‘fat mass’:ab,ti OR ‘fat free mass’:ab,ti OR ‘lean mass’:ab,ti OR ‘obese’:ab,ti OR ‘obesity’:ab,ti OR ‘underweight’:ab,ti OR ‘overweight’:ab,ti OR ‘weight status’:ab,ti OR ‘head circumference’:ab,ti OR ‘arm circumference’:ab,ti OR ‘calf circumference’:ab,ti OR ‘neck circumference’:ab,ti OR ‘thigh circumference’:ab,ti OR ‘waist circumference’:ab,ti OR ‘waist to hip ratio’:ab,ti OR ‘waist hip ratio’:ab,ti OR ‘body mass index’:ab,ti OR ‘BMI’:ab,ti OR ‘adipos*’:ab,ti OR ‘body weight’:ab,ti OR ‘body height’:ab,ti OR ‘body size’:ab,ti OR ‘body composition’:ab,ti OR ‘overnutrition’:ab,ti OR ‘wasting’:ab,ti OR ‘healthy weight’:ab,ti OR ‘skin fold*’:ab,ti OR ‘skinfold*’:ab,ti OR ‘body weight management’/exp OR ‘body weight change’/exp OR ‘weight gain*’:ab,ti OR ‘diet reduc*’:ab,ti OR ‘weight cycling’:ab,ti OR ‘weight watch*’:ab,ti OR ‘weight control*’:ab,ti OR ‘weight retention’:ab,ti OR ‘weight management’:ab,ti OR (weight NEAR/4 (decreas* OR gain* OR maint* OR reduc* OR loss* OR chang*)):ab,ti OR ‘weight chart’/exp OR ‘growth chart*’:ab,ti OR stunting:ab,ti OR stunted:ab,ti OR ‘weight for height’:ab,ti OR ‘stature for age’:ab,ti OR ‘weight for age’:ab,ti OR ‘height for age’:ab,ti OR ‘length for age’:ab,ti OR ‘weight for length’:ab,ti OR ‘failure to thrive’:ab,ti
#3 | | #1 AND #2
#4 | Limits | #3 AND ([article]/lim OR [article in press]/lim) NOT ([animals]/lim NOT ([animals]/lim AND [humans]/lim)) AND [english]/lim NOT ([conference abstract]/lim OR [conference paper]/lim OR [conference review]/lim OR [editorial]/lim OR [erratum]/lim OR [letter]/lim OR [note]/lim OR ‘retraction of publication’:ab,ti OR ‘retraction notice’:ti OR ‘retracted publication’:ab,ti OR [review]/lim OR [systematic review]/lim OR [meta analysis]/lim OR ‘practice guideline’:ti) AND [2000-2024]/py

### Database: Cochrane Central Register of Controlled Trials (CENTRAL)

Provider: John Wiley & Sons

Date(s) Searched: December 16, 2022 (initial search); December 16, 2022 -January 9, 2024 (continuous evidence monitoring)

Dates Covered: January 1, 2000 – January 9, 2024

Table A 4 Search for Cochrane CENTRAL

Search # | Concept | String
#1 | Ultra processed foods | (([mh “Fast Foods”] OR [mh “Food Handling”]) AND (process*):ti,ab,kw) OR (((ultraprocessed OR processed) NEAR/3 (food* OR product* OR “dietary pattern” OR “dietary patterns”)) OR “NOVA classification” OR “NOVA food” OR “NOVA category” OR “NOVA categories” OR (‘SIGA’ NEAR (index OR classification OR algorithm)) OR “Hyper palatable” OR “hyper palatability” OR Hyperpalat* OR “highly palatable” OR “high palatability”):ti,ab,kw
#2 | Growth, body composition, and risk of obesity | ([mh “Adipose Tissue”] OR [mh “Body Composition”] OR [mh ^”Body Weights and Measures”] OR [mh “Body Fat Distribution”] OR [mh “Body Mass Index”] OR [mh “Body Size”] OR [mh “Skinfold Thickness”] OR [mh “Waist-Hip Ratio”] OR [mh Overnutrition] OR [mh ^Growth] OR anthropometr* OR “body fat” OR “fat mass” OR “fat free mass” OR “lean mass” OR obese OR obesity OR underweight OR overweight OR “weight status” OR “head circumference” OR “arm circumference” OR “calf circumference” OR “neck circumference” OR “thigh circumference” OR “waist circumference” OR “waist to hip ratio” OR “waist hip ratio” OR “body mass index” OR BMI OR adipos* OR “body weight” OR “body height” OR “body size” OR “body composition” OR overnutrition OR wasting OR “healthy weight” OR “skin fold” OR “skin folds” OR skinfold OR skinfolds):ti,ab,kw OR ([mh “Weight Reduction Programs”] OR [mh “Body-Weight Trajectory”] OR [mh “Weight Gain”] OR [mh ^“Weight Loss”] OR [mh “Diet, Reducing”] OR “diet reduc*” OR “weight cycling” OR “weight watch*” OR “weight control*” OR “weight retention” OR “weight management”):ti,ab,kw OR ((weight NEAR/4 (decreas* OR gain* OR maint* OR reduc* OR loss* OR chang*)) OR [mh “Growth Charts”] OR “growth chart*” OR stunting OR stunted OR “weight for height” OR “stature for age” OR “weight for age” OR “height for age” OR “length for age” OR “weight for length” OR “failure to thrive”):ti,ab,kw
#3 | | #1 AND #2; In Trials. Word variations have been searched. Publication Year from 2000 to 2024.