# Appendix 1 Abbreviations

Table A 1 List of abbreviations
Abbreviation: Full name
BMI: Body mass index
HDI: Human Development Index
HHS: United States Department of Health and Human Services
NESR: Nutrition Evidence Systematic Review
RCT: Randomized controlled trial
SEP: Socioeconomic position
USDA: United States Department of Agriculture
UPF: Ultra-processed food