# References of the articles included in the systematic review

1 Kral TVE, Whiteford LM, Heo M, Faith MS. Effects of eating breakfast compared with skipping breakfast on ratings of appetite and intake at subsequent meals in 8-to 10-y-old children. Am J Clin Nutr. Feb 2011;93(2):284–284. doi:10.3945/ajcn.110.000505 21084650
2 Mehra R, Tsalikian E, Chenard CA, Zimmerman MB, Sivitz WI. Feeding frequency and appetite in lean and obese prepubertal children. Obesity. Mar 2011;19(3):560–560. doi:10.1038/oby.2010.205 20847731
3 Varley-Campbell JL, Moore MS, Williams CA. The effects of a mid-morning snack and moderate-intensity exercise on acute appetite and energy intake in 12-14-year-old adolescents. Brit J Nutr. Feb 2017;117(4):602–602. doi:10.1017/S0007114515004201 26522492
4 Zakrzewski-Fruer JK, Plekhanova T, Mandila D, Lekatis Y, Tolfrey K. Effect of breakfast omission and consumption on energy intake and physical activity in adolescent girls: a randomised controlled trial. Brit J Nutr. Sep 2017;118(5):392–392. doi:10.1017/S0007114517002148 28901889
5 Zakrzewski-Fruer JK, Seall C, Tolfrey K. Breakfast consumption suppresses appetite but does not increase daily energy intake or physical activity energy expenditure when compared with breakfast omission in adolescent girls who habitually skip breakfast: A 7-day randomised crossover trial. Nutrients. Dec 2021;13(12)doi:10.3390/nu13124261
6 Astbury NM, Taylor MA, Macdonald IA. Breakfast Consumption Affects Appetite, Energy Intake, and the Metabolic and Endocrine Responses to Foods Consumed Later in the Day in Male Habitual Breakfast Eaters. J Nutr. Jul 2011;141(7):1381–1381. doi:10.3945/jn.110.128645 21562233
7 Betts JA, Richardson JD, Chowdhury EA, Holman GD, Tsintzas K, Thompson D. The causal role of breakfast in energy balance and health: a randomized controlled trial in lean adults. Am J Clin Nutr. Aug 2014;100(2):539–539. doi:10.3945/ajcn.114.083402 24898233
8 Chowdhury EA, Richardson JD, Gonzalez JT, Tsintzas K, Thompson D, Betts JA. Six Weeks of Morning Fasting Causes Little Adaptation of Metabolic or Appetite Responses to Feeding in Adults with Obesity. Obesity. May 2019;27(5):813–813. doi:10.1002/oby.22452 30925197
9 Chowdhury EA, Richardson JD, Holman GD, Tsintzas K, Thompson D, Betts JA. The causal role of breakfast in energy balance and health: a randomized controlled trial in obese adults. Am J Clin Nutr. Mar 2016;103(3):747–747. doi:10.3945/ajcn.115.122044 26864365
10 Chowdhury EA, Richardson JD, Tsintzas K, Thompson D, Betts JA. Carbohydrate-rich breakfast attenuates glycaemic, insulinaemic and ghrelin response to lunch relative to morning fasting in lean adults. Brit J Nutr. Jul 14 2015;114(1):98–98. doi:10.1017/S0007114515001506 26004166
11 Chowdhury EA, Richardson JD, Tsintzas K, Thompson D, Betts JA. Effect of extended morning fasting upon lunch intake and associated metabolic and hormonal responses in obese adults. Int J Obesity. Feb 2016;40(2):305–305. doi:10.1038/ijo.2015.154
12 Chowdhury EA, Richardson JD, Tsintzas K, Thompson D, Betts JA. Postprandial Metabolism and Appetite Do Not Differ between Lean Adults that Eat Breakfast or Morning Fast for 6 Weeks. J Nutr. Jan 2018;148(1):13–13. doi:10.1093/jn/nxx004 29378040
13 Clayton DJ, Barutcu A, Machin C, Stensel DJ, James LJ. Effect of Breakfast Omission on Energy Intake and Evening Exercise Performance. Med Sci Sport Exer. Dec 2015;47(12):2645–2645. doi:10.1249/Mss.0000000000000702
14 Edinburgh RM, Hengist A, Smith HA, Skipping Breakfast Before Exercise Creates a More Negative 24-hour Energy Balance: A Randomized Controlled Trial in Healthy Physically Active Young Men. J Nutr. Aug 2019;149(8):1326–1326. doi:10.1093/jn/nxz018 31321428
15 Farshchi HR, Taylor MA, Macdonald IA. Deleterious effects of omitting breakfast on insulin sensitivity and fasting lipid profiles in healthy lean women. Am J Clin Nutr. Feb 2005;81(2):388–388.15699226
16 Gonzalez JT, Veasey RC, Rumbold PLS, Stevenson EJ. Breakfast and exercise contingently affect postprandial metabolism and energy balance in physically active males. Brit J Nutr. Aug 28 2013;110(4):721–721. doi:10.1017/S0007114512005582 23340006
17 Griffiths A, Deighton K, Shannon OM, Appetite and energy intake responses to breakfast consumption and carbohydrate supplementation in hypoxia. Appetite. Apr 1 2020;147doi:10.1016/j.appet.2019.104564
18 Halsey LG, Huber JW, Low T, Ibeawuchi C, Woodruff P, Reeves S. Does consuming breakfast influence activity levels? An experiment into the effect of breakfast consumption on eating habits and energy expenditure. Public Health Nutr. Feb 2012;15(2):238–238. doi:10.1017/S136898001100111x 21729464
19 LeCheminant GM, LeCheminant JD, Tucker LA, Bailey BW. A randomized controlled trial to study the effects of breakfast on energy intake, physical activity, and body fat in women who are nonhabitual breakfast eaters. Appetite. May 1 2017;112:44–51. doi:10.1016/j.appet.2016.12.041 28063876
20 Leidy HJ, Hoertel HA, Douglas SM, Higgins KA, Shafer RS. A high-protein breakfast prevents body fat gain, through reductions in daily intake and hunger, in “Breakfast skipping” adolescents. Obesity. Sep 2015;23(9):1761–1761. doi:10.1002/oby.21185 26239831
21 Leidy HJ, Ortinau LC, Douglas SM, Hoertel HA. Beneficial effects of a higher-protein breakfast on the appetitive, hormonal, and neural signals controlling energy intake regulation in overweight/obese, “breakfast-skipping,” late-adolescent girls. Am J Clin Nutr. Apr 2013;97(4):677–677. doi:10.3945/ajcn.112.053116 23446906
22 Levitsky DA, Pacanowski CR. Effect of skipping breakfast on subsequent energy intake. Physiol Behav. Jul 2 2013;119:9–16. doi:10.1016/j.physbeh.2013.05.006 23672851
23 Neumann BL, Dunn A, Johnson D, Adams JD, Baum JI. Breakfast Macronutrient Composition Influences Thermic Effect of Feeding and Fat Oxidation in Young Women Who Habitually Skip Breakfast. Nutrients. Aug 2016;8(8)doi:10.3390/nu8080490
24 Reeves S, Huber JW, Halsey LG, Horabady-Farahani Y, Ijadi M, Smith T. Experimental manipulation of breakfast in normal and overweight/obese participants is associated with changes to nutrient and energy intake consumption patterns. Physiol Behav. Jun 22 2014;133:130–135. doi:10.1016/j.physbeh.2014.05.015 24866910
25 Rosi A, Martini D, Scazzina F, Nature and Cognitive Perception of 4 Different Breakfast Meals Influence Satiety-Related Sensations and Postprandial Metabolic Responses but Have Little Effect on Food Choices and Intake Later in the Day in a Randomized Crossover Trial in Healthy Men. J Nutr. Oct 2018;148(10):1536–1536. doi:10.1093/jn/nxy160 30204905
26 Slater T, Mode WJA, Hough J, Effect of the perception of breakfast consumption on subsequent appetite and energy intake in healthy males. Eur J Nutr. Apr 2022;61(3):1319–1319. doi:10.1007/s00394-021-02727-5 34766208
27 Thomas EA, Higgins J, Bessesen DH, McNair B, Cornier MA. Usual breakfast eating habits affect response to breakfast skipping in overweight women. Obesity. Apr 2015;23(4):750–750. doi:10.1002/oby.21049 25755093
28 Veasey RC, Haskell-Ramsay CF, Kennedy DO, Tiplady B, Stevenson EJ. The Effect of Breakfast Prior to Morning Exercise on Cognitive Performance, Mood and Appetite Later in the Day in Habitually Active Women. Nutrients. Jul 2015;7(7):5712–5712. doi:10.3390/nu7075250 26184302
29 Yoshimura E, Hatamoto Y, Yonekura S, Tanaka H. Skipping breakfast reduces energy intake and physical activity in healthy women who are habitual breakfast eaters: A randomized crossover trial. Physiol Behav. May 15 2017;174:89–94. doi:10.1016/j.physbeh.2017.03.008 28284879
30 Zhang LJ, Cordeiro LS, Liu JH, Ma YS. The Association between Breakfast Skipping and Body Weight, Nutrient Intake, and Metabolic Measures among Participants with Metabolic Syndrome. Nutrients. Apr 2017;9(4)doi:10.3390/nu9040384
31 Gwin JA, Leidy HJ. Breakfast Consumption Augments Appetite, Eating Behavior, and Exploratory Markers of Sleep Quality Compared with Skipping Breakfast in Healthy Young Adults. Curr Dev Nutr. Nov 2018;2(11):nzy074. doi:10.1093/cdn/nzy074 30402594
32 Bachman JL, Raynor HA. Effects of manipulating eating frequency during a behavioral weight loss intervention: a pilot randomized controlled trial. Obesity (Silver Spring). May 2012;20(5):985–985. doi:10.1038/oby.2011.360 22173575
33 Berteus Forslund H, Klingstrom S, Hagberg H, Londahl M, Torgerson JS, Lindroos AK. Should snacks be recommended in obesity treatment? A 1-year randomized clinical trial. Eur J Clin Nutr. Nov 2008;62(11):1308–1308. doi:10.1038/sj.ejcn.1602860 17700649
34 Grangeiro ED, Trigueiro MS, Siais LO, Hypocaloric diet with lower meal frequency did not affect weight loss, body composition and insulin responsiveness, but improved lipid profile: a randomized clinical trial. Food Funct. Dec 13 2021;12(24):12594–12594. doi:10.1039/d1fo00484k 34816273
35 Huseinovic E, Winkvist A, Bertz F, Forslund HB, Brekke HK. Eating frequency, energy intake and body weight during a successful weight loss trial in overweight and obese postpartum women. Eur J Clin Nutr. Jan 2014;68(1):71–71. doi:10.1038/ejcn.2013.200 24193227
36 Meessen ECE, Andresen H, van Barneveld T, Differential Effects of One Meal per Day in the Evening on Metabolic Health and Physical Performance in Lean Individuals. Front Physiol. 2021;12:771944. doi:10.3389/fphys.2021.771944 35087416
37 Papakonstantinou E, Kontogianni MD, Mitrou P, Effects of 6 vs 3 eucaloric meal patterns on glycaemic control and satiety in people with impaired glucose tolerance or overt type 2 diabetes: A randomized trial. Diabetes Metab. Jun 2018;44(3):226–226. doi:10.1016/j.diabet.2018.03.008 29680359
38 Johnstone AM, Shannon E, Whybrow S, Reid CA, Stubbs RJ. Altering the temporal distribution of energy intake with isoenergetically dense foods given as snacks does not affect total daily energy intake in normal-weight men. Brit J Nutr. Jan 2000;83(1):7–7. doi:Doi 10.1017/S0007114500000039 10703459
39 Vander Wal JS, Waller SM, Klurfeld DM, Effect of a post-dinner snack and partial meal replacement program on weight loss. Int J Food Sci Nutr. Feb-Mar 2006;57(1–2):97–106. doi:10.1080/09637480600658369 16849118