# Summary of conclusion statements and grades

The 2025 Dietary Guidelines Advisory Committee answered the systematic review question, “What is the relationship between frequency of meals and/or snacking and energy intake?”, with the following conclusion statements.^*^ The grades reflect the strength of the evidence underlying the conclusion statements.

* A conclusion statement is carefully constructed, based on the evidence reviewed, to answer the systematic review question. A conclusion statement does not draw implications and should not be interpreted as dietary guidance.

### Children and adolescents

A conclusion statement cannot be drawn about the relationship between frequency of meals and/or snacking in children and adolescents and energy intake because of substantial concerns with heterogeneity of exposures in a small body of evidence. (Grade: Grade Not Assignable)

### Adults and older adults

A conclusion statement cannot be drawn about the relationship between breakfast consumption in adults and total daily energy intake because of substantial concerns with consistency and generalizability in the body of evidence. (Grade: Grade Not Assignable)

A conclusion statement cannot be drawn about the relationship between breakfast consumption in older adults and energy intake because there is no evidence available. (Grade: Grade Not Assignable)

A conclusion statement cannot be drawn about the relationship between number of eating occasions per day in adults and older adults and energy intake because of substantial concerns with generalizability in a small body of evidence. (Grade: Grade Not Assignable)

A conclusion statement cannot be drawn about the relationship between snacking in adults and older adults and energy intake because of substantial concerns with generalizability in the body of evidence. (Grade: Grade Not Assignable)

## Research recommendations

The Committee identified the following research recommendations that describe the research, data, and methodological advances that are needed to strengthen the body of evidence on frequency of meals and/or snacking and energy intake.

1. Develop and support prospective and/or experimental research that examines the relationship between frequency of meals and/or snacking and total daily energy intake in all age groups, including older adults, which includes a target population reflective of the geographic, racial, and socioeconomic diversity in the U.S.
2. Include details about what foods were consumed and their quality by study participants when reporting results related to frequency of meals and/or snacking and energy intake
3. Develop definitions of eating occasions, meals, and snacks as well as frameworks and reporting standards to be used consistently in research in order to increase comparability across studies and aid in the development of guidance around this topic.
4. Support research with funding from Federal and other funding agencies that provides information on types, frequency, timing, and size of meals and/or snacks in order to increase the accuracy and precision of the assessment of meal and snack frequency patterns and the ability to assess the combined and independent effects of frequency and timing of eating.
5. Provide consistency in the operational definition of frequency across studies when developing the comparisons to be examined in articles (e.g., categories of frequency comparisons vs. continuous frequency).
6. Explore all different meals and snack frequency patterns as a 24-hour eating behavior rather than isolating a meal or a snack and consider longer intervention period and follow-up.
7. Conduct studies that have enough follow up to understand the long-term impact of meals/snacks frequency patterns on energy intake.
8. Measure and assess energy intake across an entire 24-hour period in order to capture the impact of frequency of meals and snacks on an entire days’ consumption and not only on the following meal or snack.

Table 8 Evidence examining the relationship between frequency of meals and/or snacking in children and adolescents and energy intake^a^

Study and Population Characteristics | Intervention, Comparator, and Outcome(s) | Results and Summary of Findings | Study Limitations
Kral, 2011^1^; RCT-Crossover, U.S.; Baseline N=21, Analytic N=21 (Attrition: 0%); Study objective: To test the effects of consuming breakfast compared with omitting breakfast on energy intake, percentage of calories from fat, and dietary energy density at subsequent meals in children aged between 8 and 10 y; Participant characteristics at baseline: children 8-10y with normal BMI-for-age %; - Age: Mean (SD): 9.2 (0.8); - Female: 71%; - Race and/or ethnicity: White: 19%; African American: 76%; Mixed race: 5%; - Socioeconomic position: NR; - Anthropometry: Mean (SD): BMI-for-age %, 57.3 (29.4); 71 % normal weight, 29% overweight; - Physical activity: NR; - Smoking: N/A; - TEI: NR; - Usual diet at baseline: Eat breakfast daily: 91% during week and 95% on weekend; Excluded from study or analysis: BMI-for-age <5th% and >94th%; serious medical conditions known to affect food intake and body weight; any learning disability or visual or auditory impairment; any developmental, medical, or psychiatric conditions that might affect study compliance; any food allergies; or were taking medications known to affect food intake or body weight. | Intervention: Breakfast vs No Breakfast (NB); Children consumed breakfast in full over a period of 30 min in presence of a research assistant who waited in an adjacent room. Participants were allowed to drink water, if desired. Breakfast consisted of ready-to-eat breakfast cereal, 1% milk, banana, and orange juice (350 kcal, which comprised ~19% of children’s daily estimated energy requirement).; Duration: Single meal (1wk washout); Compliance: parents/caretakers were asked to complete a meal/snack report to ensure that they had complied with the study procedures.; Outcomes and assessment methods:; Children were served lunch at 11:45am and consumed ad libitum over a period of 20 min. Lunch consisted of pasta, tomato sauce, broccoli, applesauce, chocolate chip cookies, and 1% milk. Portion sizes remained constant across experimental conditions.; - Energy intake during lunch assessed by weighing all foods and beverages before and after the meal to determine the amount consumed by each child to the nearest 0.1g.; - Energy intake throughout remainder of the day: assessed via parental-report. Parents were instructed to complete a food record capturing their child’s food and beverage intake throughout the remainder of the day (away from lab). Parents received detailed training by a clinical research coordinator with written instructions and visual aids for portion size estimates.; - Total daily energy intake: sum of calories consumed at breakfast, lunch, and during the remainder of the day.; - Energy density of the food consumed at lunch (laboratory meal) and throughout the remainder of the day (self-reported intake), excluding beverages, was computed by dividing the total energy consumed from food by the total weight of food consumed. | [underlined: Energy intake at lunch (kcal).] Mean (SE); NB: 593 (50); Breakfast: 634 (50); p=0.36; [underlined: Enerav intake consumed throuqh remainder of the dav (kcal).] Mean (SE); NB: 1237 (134); Breakfast: 1207 (134); p=0.85; [underlined: Total daily enerqy intake (kcal)], Mean difference 362 more with breakfast consumption compared to NB; p=0.04; [underlined: Enerqv densitv at lunch (kcal/g)], Mean (SE); NB: 1.25 (0.06); Breakfast: 1.25 (0.06); p=0.91; [underlined: Energy densitv throuahout remainder of the day (kcal/g)], Mean (SE); NB: 2.08 (0.16); Breakfast: 2.16 (0.16); p=0.68 | Limitations:; - Methods for randomization and concealment NR; - Not sufficiently powered; - No preregistered data analysis plan; Funding:; General Mills Bell Institute of Health and Nutrition
Mehra, 2011^2^; RCT-Crossover, U.S.; Baseline N=35, Analytic N=35 (Attrition: 0%); Study objective: To determine the effect of feeding frequency on appetite in prepubertal children with normal weight and obesity.; Participant characteristics at baseline: prepubertal children (6-10y) with normal weight or obesity; - Age: Mean ~8.5y; - Female: 53%; - Race and/or ethnicity: White: 83%; - Socioeconomic position: NR; - Anthropometry: BMI%, Mean (SD), 56.67 (5.42) in lean and 97.76 (0.16) in obesity; - Physical activity: NR; - Smoking: N/A; - TEI: ~1580 kcal in children with normal weight; ~2300 kcal in children with obesity; - Usual diet at baseline: NR; Excluded from study or analysis: diabetes or any other chronic disease; any syndrome involving abnormal metabolism or eating; use of steroids, stimulant medications, or any other medication known to increase or decrease appetite; signs of puberty on examination; <6 or >10y at first study visit | Intervention: 5 vs 3 meals per day; Children were assigned to one of two isocaloric meal patterns (5-meal or 3-meal) and asked to consume the meal within 30min. The 5-meal pattern was 20% total daily energy needs at Sam, 10am, 12pm, 2pm and 5pm. The 3-meal pattern was 33% of total daily energy needs at 8am, 12pm, and 5pm. No additional foods or beverages including water were provided between meals. Children were asked to eat their last food no later than 8pm the night before coming into the lab; Duration: 1 day (2d-2wk washout); Compliance: “All subjects complied with the treatments and followed the protocol”; Outcomes and assessment methods:; - Same day as intervention; - Children were offered ice cream ad libitum (up to a predetermined upper limit of 8 quarter-cup scoops) 2hr following the last feeding. Ice cream consumption was determined by the difference in weights of the bowls before and after consumption of the amount desired. Energy intake of ice cream was calculated. | [underlined: Total ice cream consumed (kcal)], Mean (SE); Children with obesity (n=17): 73.0 (37 4) more after 5-meal compared to 3-meal; Children with normal weight (n=18): 47.1 (27.8) less after 5-meal compared to 3-meal; Group x Meal pattern interaction: p=0.014 | Limitations:; - Methods for randomization and concealment NR; - No power calculation; - No pre registered data analysis plan; Funding:; NIH; Iowa Affiliate of the Fraternal Order of the Eagles; VA Medical Affairs; Genentech Foundation
Varley-Campbell, 2017^3^; RCT-Crossover, UK; Baseline N=40, Analytic N=38 (Attrition: 5%); Study objective: To investigate whether an energy-controlled mid-morning snack, an increased energy expenditure from a moderate-intensity exercise session, or a combined protocol can alter acute subjective feelings of appetite, and whether acute lunchtime El would be altered between conditions.; Participant characteristics at baseline: adolescents; - Age: Mean~13y; - Female: 47%; - Race and/or ethnicity: NR; - Socioeconomic position: NR; - Anthropometry: BMI, Mean (SD), 15.3 (2.3) kg/m^2^ in girls, 18.4 (2.1) in boys; - Physical activity: EE 1 MJ for EX and EX+SN groups; - Smoking: NR; - TEI: Breakfast not included in El (constant throughout).; - Usual diet at baseline: External eating, Mean (SD), 2.01 (0.55) boys and 1.95 (0.41) girts; Excluded from study or analysis: history of diabetes or other metabolic disorders known to affect intermediary metabolism | Intervention: Snacking: 1 of 4 conditions, all completed in a temporary lab setup within the school; Control (CON): control condition of no snack and no exercise; Snack (SN): mid-morning snack; Exercise (EX): moderate-intensity exercise; Snack + Exercise (SN+EX): mid-morning snack and moderate-intensity exercise; Duration: 1 day (7-28d washout); Compliance: NR; Outcomes and assessment methods:; - Same day as intervention; - Participants were given pizza to eat ad libitum during the duration of lunch break (40min).; - Energy intake from lunch was calculated by weighing intake of each lunch plate.; - Relative energy intake was calculated for each condition (El + 1 MJ for SN and SN+EX conditions, and El −1 MJ for EX and SN+EX conditions) to take daily energy balance into consideration. | [underlined: Enerqy intake at lunch (kcal)], Mean (SE); Between group difference data NR (figure only), p=0.202; Group x sex interaction: p=0.583; [underlined: Relative energy intake (kcal)], Mean (SE); Between group difference: data NR (figure only), p<0.001; Group x sex interaction: p=0.583; [underlined: Relative enerav intake (kcal)], Mean difference (SEM); SN+EX vs EX: 191.2 (47.8); higher in SN+EX, p<0.05; SN vs CON: data NR, NS | Limitations:; - Methods for randomization and concealment NR; - No preregistered data analysis plan; Funding:; Kelloggs Ltd
Zakrzewski-Fruer, 2017^4^; RCT-Crossover, UK; Baseline N=49, Analytic N=40 (Attrition: 18%); Study objective: To compare the effect of three consecutive weekdays of breakfast omission with standardized breakfast consumption on free-living energy intake and physical activity in girls aged 11-15y.; Participant characteristics at baseline: adolescent girls; - Age: Mean (SD): 13.3 (0.8)y; - Female: 100%; - Race and/or ethnicity: NR; - Socioeconomic position: NR; - Anthropometry: Mean (SD): BMI 21.5 (5.0) kg/m^2^; - Physical activity: MVPA ~7% of total wear time; - Smoking: NR; - TEI: NR; Usual diet at baseline: Usual breakfast: Mean (SD), 183 (105) kcal/d; Excluded from study or analysis: health-related issues identified from health screening questionnaire; unable to walk or wear a physical activity monitor on their wrist; did not attend breakfast intervention on all days; did not abstain from all foods and beverages until 10:30am (for breakfast skipping group); consumed <80% of recommended daily energy intake of breakfast intervention; did not record their diet and wear accelerometer as specified | Intervention: Breakfast vs No Breakfast (NB); The breakfast group consumed breakfast at school within 30 min (8:15-8:45am), which consisted of ready-to-eat cereal, semi-skimmed milk, and orange juice (500kcal, equating to ~22-26% of daily energy requirements). The NB group arrived at school in the fasted state and were provided with 375 mL water at school; they were instructed to consume no food or drink except water from 9pm the previous day to 10:30am the following morning).; Duration: 3 consecutive weekdays (4d or 11d washout); Compliance: Excluded from analysis if non-compliant; Outcomes and assessment methods:; - Same day as intervention; - Energy intake assessed using food diaries combined with digital photographs of all foods and beverages consumed | [underlined: Energy intake (kcal)], Mean (SD); Total daily (8:00am-9pm):; NB: 1257 (339); Breakfast: 1608 (295); p<0.0005; Post-breakfast (10:30am-9pm):; NB vs breakfast: 115 (313) kcal higher in NB group; p=0.025 | Limitations:; - No preregistered data analysis plan; Funding:; No external funding
Zakrzewski-Fruer, 2021^5^; RCT-Crossover, UK; Baseline N=23, Analytic N=11 (Attrition: 52%); Study objective: To compare the effects of seven days of breakfast consumption with breakfast omission on free-living physical activity energy expenditure in adolescent girls classified as habitual breakfast skippers.; Participant characteristics at baseline: adolescent girls; - Age: Mean (SD): 13.3 (0.8)y; - Female: 100%; - Race and/or ethnicity: NR; - Socioeconomic position: NR; - Anthropometry: Mean (SD): BMI 21.3 (3.2) kg/m^2^; - Physical activity: NR; - Smoking: NR; - TEI: NR; - Usual diet at baseline: Habitually skips breakfast: Mean (SD), 5 (1) days/wk; Excluded from study or analysis: health-related issues identified from health screening questionnaire; unable to walk or wear a combined heart rate and accelerometer on their chest; classified as habitual breakfast consumers; did not consume their breakfast on all 7 days (breakfast group) or did not confirm verbally that they had not consumed energy-providing nutrients before 10:30am on all 7 days (NB group). | Intervention: Breakfast vs No Breakfast (NB); The breakfast group consumed a standardized breakfast at home before 9:00am; breakfast consisted of ready-to-eat cereal with semi-skimmed milk, orange or apple juice, and optional raisins. Food items were provided in prepackaged containers with marked beakers to measure milk and juice. The NB group abstained from all energy-providing nutrients before 10:30am. Both groups could eat ad libitum from 10:30am onward.; Breakfast was defined as consumption with 2-3hr of waking, typically no later than 10:00am.; Duration: 7 consecutive days (7-10d washout); Compliance: Excluded from analysis if non-compliant; Outcomes and assessment methods:; - Same day as intervention; Energy intake assessed using food diaries combined with digital photographs of all foods and beverages consumed | [underlined: Enerqy intake (kcal)], Mean (95% Cl); Total daily intake (wake time to bed time); NB: 975 (732, 1299); Breakfast: 1005 (755, 1339); p=NS; Post-breakfast intake; (10:30am-3:30pm, 3:30pm to bed time); NB: 484 (292, 803), 389 (235, 645); Breakfast: 413 (249, 684), 282 (170, 468); p=NS | Limitations:; - Differences in attrition; - Not sufficiently powered; - No preregistered data analysis plan; Funding:; Nutrition Society Summer Studentship Scheme; National Institute for Health Research Leicester Biomedical Research Centre

a Abbreviations: BMI: body mass index; CON: control; d: day; EI: energy intake; EX: exercise; kcal: kilocalories; MJ: megajoule; MVPA: moderate to vigorous physical activity; NB: no breakfast; NR: not reported; NS: not significant; SE: standard error; SD: standard deviation; SN: snack; TEI: total energy intake; wk: week; y: year

Table 9 Risk of bias for randomized controlled trials examining frequency of meals and/or snacking in children and adolescents and energy intake^a^

Article | Randomization | Period and carryover effects | Deviations from intended interventions (per-protocol) | Missing outcome data | Outcome measurement | Selection of the reported result | Overall risk of bias
Krai, 2011 ^1^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Mehra, 2011 ^2^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Varley-Campbell, 2017 ^3^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Zakrzewski-Fruer, 2017 ^4^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Zakrzewski-Fruer, 2021 ^5^ | LOW | LOW | LOW | HIGH | LOW | LOW | HIGH

a Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898. doi:10.1136/bmj.l4898 31462531 .)

Table 10 Evidence examining the relationship between breakfast consumption in adults and energy intake^a^

Study and Population Characteristics | Intervention, Comparator, and Outcome | Results | Study Limitations
RANDOMIZED CONTROLLED TRIALS
Astbury, 2011^6^; RCT-Crossover, UK; Baseline N=12, Analytic N=12 (Attrition: 0%); Study objective: To compare the effects of consuming breakfast with omitting breakfast on energy intake at a lunchtime test meal, subjective appetite responses, and the metabolic and endocrine responses to foods consumed later in the day in men who regularly eat breakfast.; Participant characteristics at baseline: male habitual breakfast eaters; - Age: 24.3 (7.3)y; - Female: 0%; - Race and/or ethnicity: NR; - Socioeconomic position: NR; - Anthropometry: BMI 23.5 (1.7) kg/m^2^; - Physical activity: NR; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: All habitually consumed breakfast (inclusion criteria); Excluded from study oranalysis: aged <18 or >45y; BMI <19 or >25 kg/m^2^; female; irregular breakfast eater (consuming ready-to-eat cereal or continental style breakfast on <5 of 7 d); history of serious disease or currently taking any medications; current dieters; those with a recent weight loss or gain (±3 kg in the past 6mo); restrained eaters (score >7 for restraint on Three Factor eating Questionnaire); those with symptoms of clinical depression | Intervention: Breakfast vs No Breakfast (NB); Breakfast: cereal and milk (10% of daily energy requirement) consumed within 20min; water ad libitum; Breakfast provided included Rice Krispies (Kelloggs) and semi skimmed milk (1.7% fat; cereak:milk ratio was 30g:125 mL) equivalent to 10% of the participant’s DER. Each breakfast contained 14, 14, and 72% energy from protein, fat, and carbohydrate, respectively. NB: no breakfast (water ad libitum) Both groups were given a 400mL preload (protein; Duration: 1d (>1wk washout); Compliance: NR; Outcomes and assessment methods:; - Same day as intervention; - Participants were provided with an ad libitum pasta lunch in pre-weighed servings; participants voluntarily terminated the lunch meal. Energy intake was determined from the weight of food consumed. | [underlined: Energy intake (kcal)], Mean (SEM); Lunch; NB: 1377 (96); Breakfast: 1171 (109); p<0.01; Breakfast + Preload + Lunch; NB: 1632 (96); Breakfast: 1625 (109); p=NS | Limitations:; - Methods for randomization and concealment NR; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; Funding:; Mars UK
Betts, 2014^7^; RCT-Parallel, Bath Breakfast Project, UK; Baseline N=38, Analytic N=33 (Attrition: 13%); Study objective: To conduct a randomized controlled trial examining causal links between breakfast habits and all components of energy balance in free-living humans.; Participant characteristics at baseline: lean adults; - Age: 36 (11)y; - Female: 64%; - Race and/or ethnicity: NR; - Socioeconomic position: NR; - Anthropometry: BMI 22.4 (2.2) kg/m^2^; - Physical activity: NR; - Smoking: NR; - TEI: ~2400 kcal/d; - Habitual diet at baseline: 79% habitual breakfast consumers (>50 kcal intake within 2hr of waking on ≥4d/wk); Excluded from study or analysis: BMI <18 or >25 kg/m^2^, not weight stable (>1 kg body mass within past 6mo), metabolic disorders, non-standard sleep-wake cycle (e.g., shift workers), anticipated changes in diet and/or physical activity habits during study period, pregnant or breastfeeding, condition or behavior deemed to pose undue personal risk or introduce bias into experiment | Intervention: Breakfast vs No Breakfast (NB); Breakfast (n=16): consumed >700 kcal before 11am daily, with at least half consumed within 2hr of waking; Foods/calories consumed were self-selected, but given examples NR; ≥700 kcal; NB (n=17): extended overnight fast by abstaining from ingesting energy-providing nutrients (i.e., plain water only) until 12pm each day; Duration: 6wk; Compliance: confirmed via self-report and continuous glucose monitoring; Outcomes and assessment methods:; - At baseline, 6wk; - Energy intake estimated from directly weighed food diaries. Participants were provided with a set of food-weighing scales and trained by staff on how to record food intake. | [underlined: Enerav intake (kcal)], Mean (SE); Within group: baseline, 6wk; NB: 2169 (490), 2214 (584); Breakfast: 2715 (565), 2745 (658); Between groups: p=0.01 at baseline p-0.02 at 6wk; [underlined: Energy intake over 6wk period (kcal).] Mean (SE); NB: 2191 (494); Breakfast: 2730 (573); p=0.007 | Limitations:; - Water/Beverages were not accounted for in exposure assessment; Funding:; Biotechnology and Biological Sciences Research Council
Chowdhury, 2015^10^; RCT-Crossover, Bath Breakfast Project, UK; Baseline N=38, Analytic N=34 (Attrition: 11%); Study objective: To examine acute effects of extended morning fasting upon subsequent energy intake and metabolic/hormonal responses; Participant characteristics at baseline: lean adults; - Age 36 (11)y; - Female: 60%; - Race and/or ethnicity: NR; - Socioeconomic position: NR; - Anthropometry: BMI 22.7 (2.5) kg/m^2^; - Physical activity: NR; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: 77% habitual breakfast consumers (>50 kcal intake within 2hr of waking on ≥4d/wk); Excluded from study or analysis: aged <21 or >60y, BMI <18 or >25 kg/m^2^, not weight stable (>1 kg body mass within past 6mo), metabolic disorders, non-standard sleep-wake cycle (e.q., shift workers) | Intervention: Breakfast vs No Breakfast (NB); Breakfast: corn flakes, 2% milk, toasted white bread, margarine, and fresh orange juice (469±57 kcal; 70% carbohydrate, 17% fat and 13% protein) consumed within 15 minutes. Overnight fasting duration was ≥11h.; NB: no breakfast; unclear if participants were allowed water. Overnight fasting duration was ≥14.5h.; Duration: 1d (3-28d washout); Compliance: NR; Outcomes and assessment methods:; - Same day as intervention; - Participants were provided with ad libitum lunch 3hr after breakfast. Energy intake was measured based on volume consumed. | [underlined: Energy intake (kcal)], Mean (SD); Lunch; NB: 929 (317); Breakfast: 776 (349); p<0.01; Breakfast + Lunch; NB: 929 (317); Breakfast: 1246 (380); p<0.001 | Limitations:; - Methods for randomization and concealment NR; - Water/Beverages were not accounted for in exposure assessment; Funding:; Biotechnology and Biological Sciences Research Council
Chowdhury, 2016a^9^; RCT-Parallet, Bath Breakfast Project, UK; Baseline N=23, Analytic N=22 (Attrition: 4%); Study objective: To examine causal links between breakfast habits and components of energy balance in free-living humans with obesity; Participant characteristics at baseline: adults with obesity; - Age: 44 (10)y; - Female: 65%; - Race and/or ethnicity: NR; - Socioeconomic position: NR; - Anthropometry: BMI 33.7 (4.9) kg/m^2^; - Physical activity: NR; - Smoking: NR; - TEI: ~2600 kcal/d; - Habitual diet at baseline: 61% habitual breakfast consumers (>50 kcal intake within 2hr of waking on ≥4d/wk); Excluded from study or analysis: aged <21 or >60y, not weight stable (>2% within past 6mo), shift workers, irregular menstrual cycle/contraceptive use (if relevant), anticipated changes in diet and/or physical activity habits during study period, pregnant or breastfeeding, condition or behavior deemed to pose undue personal risk or introduce bias into experiment | Intervention: Breakfast vs No Breakfast (NB); Breakfast (n=11): consumed ≥700 kcal before 11am daily, with at least half consumed within 2hr of waking; NB (n=11): extended overnight fast by abstaining from ingesting energy-providing nutrients (i.e., plain water only) until 12pm each day.; Foods/calories consumed were self-selected, but given examples NR; ≥700 kcal; Duration: 6wk; Compliance: confirmed via self-report and continuous glucose monitoring; Outcomes and assessment methods:; - At baseline, 6wk; - Energy intake estimated from directly weighed food diaries. Participants were provided with a set of food-weighing scales and trained by staff on how to record food intake. | [underlined: Enerqy intake (kcal/d)]. Mean (SE); Within group: baseline, 6wk; NB: 2459 (780), 2303 (792); Breakfast: 2820 (595), 2618 (833); Between groups: p=0.2 at baseline; p=0.4 at 6wk; [underlined: Enerqy intake over 6wk period (kcal)], Mean (SE); NB: 2381 (777); Breakfast: 2719 (683); p=0.3 | Limitations:; - Water/Beverages were not accounted for in exposure assessment; Funding:; Biotechnology and Biological Sciences Research Council
Chowdhury, 2016b^11^; RCT-Crossover, Bath Breakfast Project, UK; Baseline N=24, Analytic N=24 (Attrition: 0%); Study objective: To examine energy intake, as well as metabolic and hormonal responses to acute morning fasting in individuals with obesity; Participant characteristics at baseline: adults with obesity; - Age 44 (10)y; - Female: 16%; - Race and/or ethnicity: NR; - Socioeconomic position: NR; - Anthropometry: BMI 33.5 (4.7) kg/m^2^; - Physical activity: NR; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: 14% habitual breakfast consumers (>50 kcal intake within 2hr of waking on ≥4d/wk); Excluded from study or analysis: not weight stable (>2% within past 6mo), non-standard sleep-wake cycle (e g., shift workers), metabolic disorders, taking medications known to affect appetite regulation, irregular menstrual cycle/contraceptive use (if relevant), anticipated changes in diet and/or physical activity habits during study period, pregnant or breastfeeding, condition or behavior deemed to pose undue personal risk or introduce bias into experiment | Intervention: Breakfast vs No Breakfast (NB); Breakfast: cereal, milk, toast, orange juice (521±94 kcal) consumed within 15 minutes; NB: no breakfast; unclear if participants were allowed water; Duration: 1d (3-28d washout); Compliance: NR; Outcomes and assessment methods:; - Same day as intervention; - Participants were provided with ad libitum lunch 3hr after breakfast. Energy intake was measured based on volume consumed. | [underlined: Energy intake (kcal)], Mean (SD); Lunch; NB: 869 (354); Breakfast: 817 (325); p=0.1; Breakfast + Lunch; NB < Breakfast: −469 (−393, −545); p<0.01 | Limitations:; - Methods for randomization and concealment NR; - Water/Beverages were not accounted for in exposure assessment; Funding:; Biotechnology and Biological Sciences Research Council
Chowdhury, 2018^12^; RCT-Parallel, Bath Breakfast Project, UK; Baseline N=31, Analytic N=31 (Attrition: 0%); Study objective: To examine if daily breakfast consumption or fasting until noon modifies the acute metabolic and appetitive responses to a fixed breakfast and ad libitum lunch; Participant characteristics at baseline: lean adults; - Age ~35.5 (11)y; - Female: 61%; - Race and/or ethnicity: NR; - Socioeconomic position: NR; - Anthropometry: BMI ~22 kg/m^2^; - Physical activity: NR; - Smoking: NR; - TEI: NR; - Habitua! diet at baseline: 81% habitual breakfast consumers (>50 kcal intake within 2hr of waking on ≥4d/wk); Excluded from study or analysis: BMI <18 or >25 kg/m^2^, not weight stable (>1 kg body mass within past 6mo), metabolic disorders, non-standard sleep-wake cycle (e.g., shift workers), anticipated changes in diet and/or physical activity habits during study period, pregnant or breastfeeding, condition or behavior deemed to pose undue personal risk or introduce bias into experiment | Intervention: Breakfast vs No Breakfast (NB); Breakfast (n=15): consumed ≥700 kcal before 11am daily, with at least half consumed within 2hr of waking; NB (n=16): extended overnight fast by abstaining from ingesting energy-providing nutrients (i.e., plain water only) until 12pm each day; Duration: 6wk; Compliance: NR; Outcomes and assessment methods:; - At baseline, 6wk; - Participants were provided with ad libitum lunch 3hr after breakfast. Energy intake was measured based on volume consumed. | [underlined: Energy intake (kcal),] Mean (SE); Lunch; NB vs Breakfast: p>0.2; Breakfast + Lunch; Within group: baseline, 6wk; NB: 1150 (341), 1177 (422); Breakfast: 1291 (377), 1368 (461); p-value NR | Limitations:; - Water/Beverages were not accounted for in exposure assessment; Funding:; Biotechnology and Biological Sciences Research Council
Chowdhury, 2019^8^; RCT-Parallel, Bath Breakfast Project, UK; Baseline N=22, Analytic N=22 (Attrition: 0%); Study objective: To determine the effects of sustained morning fasting or breakfast consumption on metabolism, energy intake, and appetite in healthy adults with obesity; Participant characteristics at baseline: adults with obesity; - Age: 43.5 (10)y; - Female: 64%; - Race and/or ethnicity: NR; - Socioeconomic position: NR; - Anthropometry: BMI ~33 kg/m^2^; - Physical activity: NR; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: 59% habitual breakfast consumers (>50 kcal intake within 2hr of waking on ≥4d/wk); Excluded from study or analysis: BMI<30 kg/m^2^, not weight stable (>2% within past 6mo), non-standard sleep-wake cycle (e.g., shift workers), metabolic disorders, irregular menstrual cycle/contraceptive use (if relevant), anticipated changes in lifestyle durinq study period | Intervention: Breakfast vs No Breakfast (NB); Breakfast (n=11): consumed ≥700 kcal before 11am daily, with at least half consumed within 2hr of waking; NB (n=11): extended overnight fast by abstaining from ingesting energy-providing nutrients (i.e., plain water only) until 12pm each day; Duration: 6wk; Compliance: NR; Outcomes and assessment methods:; - At baseline, 6wk; - Participants were provided with ad libitum lunch 3hr after breakfast. Energy intake was measured based on volume consumed. | [underlined: Enerqv intake (kcal)], Mean (SEM); Lunch; Within group: baseline, 6wk; NB: 735 (330), 750 (284); Breakfast: 893 (313), 779 (323); Group x trial interaction: p=0.13; Breakfast + Lunch; Within group: baseline, 6wk; NB: 1272 (331), 1286 (274); Breakfast: 1418 (350), 1305 (366); p-value NR | Limitations:; - Water/Beverages were not accounted for in exposure assessment; Funding:; Biotechnology and Biological Sciences Research Council
Clayton, 2015^13^; RCT-Crossover, UK; Baseline N=10, Analytic N=10 (Attrition: 0%); Study objective: To examine the effect of breakfast omission and consumption on subsequent energy intake and evening exercise performance 4hr after provision of an ad libitum lunch; Participant characteristics at baseline: male habitual breakfast eaters; - Age 22 (3)y; - Female: 0%; - Race and/or ethnicity: NR; - Socioeconomic position: NR; - Anthropometry: BMI 23.5 (3.2) kg/m^2^; - Physical activity: All recreationally active (<10hr/wk); - Smoking: NR; - TEI: NR; - Habitual diet at baseline: All habitual breakfast eaters; Excluded from study or analysis: NR | Intervention: Breakfast vs No Breakfast (NB); Breakfast: standardized breakfast meal based on 25% of estimated daily energy requirements (733 ± 46 teal) consumed in entirety within 30min; included crisped rice cereal, semi-skimmed milk, wholemeal toast, margarine, strawberry jam, orange juice, and water; NB: water only; Duration: 1d (≥1wk washout); Compliance: NR; Outcomes and assessment methods:; - Same day as intervention; - Participants were provided with an ad libitum lunch buffet around 12:30pm and an ad libitum pasta dinner around 7pm. Ad libitum water and low-energy squash were available upon request throughout the study period and were provided with each buffet meal. Meals were served in the lab and participants were given 30min to consume each meal. They were instructed not to eat or drink anything other than plain water until they went to bed. Energy intake was calculated by weighing the food before and after consumption. | [underlined: Energy intake (kcal)], Mean (SD); Lunch; NB: 1387 (434); Breakfast: 1188 (475); p<0.01; Dinner; NB: 1406 (345); Breakfast: 1520 (390); p=0.052; Lunch and dinner; NB: 2793 (452); Breakfast: 2708 (506); p=0.196; Total at breakfast, lunch, and dinner; NB: 2793 (452); Breakfast: 3447 (539); p<0.05 | Limitations:; - Methods for randomization and concealment NR; - No power calculation; - No preregistered data analysis plan; Funding:; National Institute for Health Research Diet, Lifestyle, and Physical Activity Biomedical Research Unit (University Hospitals of Leicester and Loughborough University)
Edinburgh, 2019^14^; RCT-Crossover, UK; Baseline N=12, Analytic N=12 (Attrition: 0%); Study objective: To investigate the rale of carbohydrate availability during exercise on net energy balance over 24hr; Participant characteristics at baseline: physically active young men; - Age: 23 (3)y; - Female: 0%; - Race and/or ethnicity: NR; - Socioeconomic position: NR; - Anthropometry: BMI 23.6 (2.0) kg/m^2^; - Physical activity: NR; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: NR; Excluded from study or analysis: history of metabolic disease, any condition that may have posed undue personal risk to the participant or introduced bias to the study | Intervention: Breakfast/Rest (BR) vs Breakfast/Exercise (BE) vs Exercise/No Breakfast (NBE); BR: porridge breakfast (refined oats/semi-skimmed milk) followed by 3hr rest; BE: porridge breakfast (refined oats/semi-skimmed milk) followed by 2hr rest and 1 hr cycling; NBE: no breakfast (water only) followed by 2hr rest and 1hr cycling; The breakfast meals provided 431kcal, 65g CHO, 11g Fat, 19g PRO.; Duration: 1d (7-30d washout); Compliance: NR; Outcomes and assessment methods:; - Same day as intervention; - Participants were provided with a researcher-weighed ad libitum lunch and the remaining food was weighed to calculate energy intake at lunch. Participants were also provided with a free-living food package to eat ad libitum (in addition to water). The remaining food was weighed to calculate free-living energy intake. | [underlined: Energy intake (kcal),] Mean difference (normalized 95% Cl); At lunch; NBE > BE: 166 (−27, 308), p=NS; Breakfast + lunch; NBE < BE: 265 (123, 407), p<0.01; Free-living (after lunch); NBE vs BE: data NR (figure only); Breakfast + lunch + free-living; NBE < BE: 393 (276, 510), p<0.01 | Limitations:; - Water/Beverages were not accounted for in exposure assessment; Funding:; European Society for Clinical Nutrition and Metabolism; Rank Prize Funds
Farshchi, 2005a^15^; RCT-Crossover, UK; Baseline N=10, Analytic N=10 (Attrition: 0%); Study objective: To investigate the effect of omitting breakfast on energy intake, resting energy expenditure, and circulating glucose, lipid, and insulin concentrations in lean healthy women.; Participant characteristics at baseline: healthy, lean women; - Age 25.5 (5.7)y; - Female: 100%; - Race and/or ethnicity: NR; - Socioeconomic position: NR; - Anthropometry: BMI 23.2 (1.6) kg/m^2^; - Physical activity: NR; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: All reported consuming breakfast regularly; Excluded from study or analysis: aged <19 or >38y, irregular menstruation (if not taking oral contraceptive pill); pregnant or lactating; self-reported history of hypercholesterolemia, hyperglycemia, or any serious medical conditions; reported that they were dieting or experiencinq depression | Intervention: Breakfast vs No Breakfast (NB); Breakfast: consumed whole-grain breakfast cereal with 2% milk between 7-8am. They also consumed a mid-morning snack, a 48g chocolate-cove red cookie (Kit Kat; Nestle) between 10:30-11am, and 2 additional meals and 2 snacks as usual.; NB: did not consume breakfast. Unclear if they were allowed to drink water. They consumed a mid-morning snack, a 48g chocoiate-covered cookie (Kit Kat; Nestle) between 10:30-11am and the whole-grain breakfast cereal at 12pm, and 2; Duration: 14d (2wk washout); Compliance: “All subjects reported having adhered to the appropriate meal patterns during the 2 interventions”; Outcomes and assessment methods:; - During the intervention; - Total energy intake was assessed using 3d food intake records (2 weekdays and 1 weekend) | [underlined: Total energy intake (kcal) during intervention period], Mean (SD); NB: 1756.69 (155.35); Breakfast: 1665.87 (141.01); p=0.001 | Limitations:; - Methods for randomization and concealment NR; - Unclear if outcome assessors were aware of intervention assignment; - No power calculation; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; Funding:; Ministry of Health and Medical Education (Islamic Republic of Iran); School of Biomedical Sciences at the University of Nottingham
Gonzalez, 2013^16^; RCT-Crossover, UK; Baseline N=12, Analytic N=12 (Attrition: 0%); Study objective: To examine the impact of breakfast and exercise on postprandial metabolism, appetite and macronutrient balance; Participant characteristics at baseline: physically active males; - Age: 23.2 (4.3)y; - Female: 0%; - Race and/or ethnicity: NR; - Socioeconomic position: NR; - Anthropometry: BMI 24.5 (2.0) kg/m^2^; - Physical activity: All exercised >30min 5x/wk; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: NR; Excluded from study or analysis: self-reported as physically inactive (<30min of moderate activity 5x/wk); restrained eaters (score of .11 on Three Factor Eating Questionnaire); any metabolic disorders or on medications | Intervention: Breakfast/Rest (BR) vs Breakfast/Exercise (BE) vs No Breakfast/Rest (NBR) vs No Breakfast/Exercise (NBE); BR: breakfast consumption followed by rest; BE: breakfast consumption followed by exercise; NBR: rest without breakfast (water only); NBE: exercise without breakfast (water only); Breakfast consisted of 72g oats and 360ml semi-skimmed milk and provided 444 kcal; 17 % protein, 60 % carbohydrate and 23 % fat.; Duration: 1d (≥1wk washout); Compliance: NR; Outcomes and assessment methods:; - Same day as intervention; - All participants received chocolate milk test drinks within 20 minutes of exercise termination (500 ml_, 120 kcal). Participants were provided with a researcher-weighed ad libitum lunch and the remaining food was weighed to calculate energy intake at lunch. | Energy intake (kJ). Mean (SE); During lunch; Between group difference: data NR (figure only); p=0.78; Breakfast + test drink + lunch; NBR< BR: p<0.001; NBE<BE:p<0.001 | Limitations:; - No power calculation; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; Funding:; No external funding
Griffiths, 2020^17^; RCT-Crossover, UK; Baseline N=12 (study 1); 11 (study 2), Analytic N=12 (study 1); 11 (study 2) (Attrition: 0%); Study objective: [underlined: Study 1]: To determine the appetite, acylated ghrelin and energy intake response to breakfast consumption and omission in acute normobaric hypoxia (fraction of inspired oxygen ~11.7%, 4300 m); [underlined: Study 2]: To determine the appetite, acylated ghrelin and energy intake response to carbohydrate supplementation after both breakfast consumption and omission in hypoxia.; Participant characteristics at baseline: physically active males; - Age: 23 (3)y; - Female: 0%; - Race and/or ethnicity: NR; - Socioeconomic position: NR; - Anthropometry: Study 1 Weight, 79.8 (13.1)kg; Study 2 Weight 76.6 (7.0)kg; - Physical activity: All physically active; - Smoking: All nonsmokers; - TEI: NR; - Habitual diet at baseline: NR; Excluded from study or analysis: smokers, hypertensive, diabetes, thyroid disorder, sickle cell trait, food allergies, taking medication, travelled to an altitude of >1500m within previous 3mo; for Study 2, participants also were required to have a normal baseline 12 lead electrocardiogram | Intervention: Breakfast vs No Breakfasl (NB); Breakfast group consumed standardized breakfast (rolled oats, semi-skimmed milk, orange juice; 535 kcal); NB group did not consume breakfast (unclear if water was allowed); Each breakfast/NB condition was done under normoxia and hypoxia conditions.; In study 2, both groups consumed a carbohydrate (CHO) or placebo (PLA) beverage supplement 1 hr after breakfast.; Duration: 1d (≥1wk washout); Compliance: NR; Outcomes and assessment methods:; - Same day as intervention; - Participants were provided with an ad libitum post-exercise lunch and water. Energy intake was determined by weighing food before and after consumption. | [underlined: STUDY 1]; [underlined: Energy intake (kcal)], Mean (SD); Lunch; Hypoxia NB vs Breakfast, p=0.40 Normoxia: NB vs Breakfast, p=0.99; Total including breakfast; Hypoxia; NB: 1293 (395); Breakfast: 1706 (489); p=0.02; Normoxia; NB: 1590 (500); Breakfast: 2217 (489); p<0.01; [underlined: STUDY 2]; [underlined: Energy intake (kcal)], Mean (SD); Lunch; NB-CHO: 1497 (615); NB-PLA: 1476 (531); Breakfast-CHO: 1480 (677); Breakfast-PLA: 1304 (471); p=0.26; Total including breakfast and beverage supplement; NB-CHO: 1926 (615); NB-PLA: 1476 (531); Breakfast-CHO: 2443 (677); Breakfast-PLA: 1839 (471); NB-CHO < Breakfast-CHO: p<0 01; NB-PLA < Breakfast-PLA: p=0.02 | Limitations:; - Methods for randomization and concealment NR; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; Funding:; No external funding
Gwin, 2018^31^; RCT-Crossover, U.S.; Baseline N=19, Analytic N=13 (Attrition: 32%); Study objective: To examine the effects of consuming a high-protein breakfast compared with breakfast skipping on markers of appetite, satiety, food reward, and food intake in healthy young adults; Participant characteristics at baseline: healthy young adults; - Age 23.5 (0.9)y; - Female: 54%; - Race and/or ethnicity: NR; - Socioeconomic position: NR; - Anthropometry: BMI 23.6 (0.6) kg/m^2^; - Physical activity: NR; - Smoking: All nonsmokers; - TEI: NR; - Habitual diet at baseline: 92% habitual breakfast consumers; Excluded from study or analysis: age <20 or >32y; BMI <22 or >30 kg/m^2^; smoker or user of tobacco products; generally unhealthy (as assessed by medical history questionnaire); 5pregnant or lactating in the past 6 mo; clinically diagnosed with an eating disorder; metabolic, hormonal, and/or neural conditions, diseases, or medications that influence metabolism or food intake; known bleeding disorders; currently or previously (in the past 6 mo) following a weight-loss or other special diet; weight loss or gain (>4.5 kg) in the past 6 mo; abnormal cognitive restraint; rating of <5 showing “neither like nor dislike” on a 9-point hedonic scale rating for the study breakfasts; clinically diagnosed with obstructive sleep apnea or insomnia; participates in shiftwork | Intervention: Breakfast vs No Breakfast (NB); Breakfast: pre-prepared (340kcal) high-protein breakfast meals consumed at home between 7-8:30am with 30 g protein, 36 g carbohydrate, 9 g fat; Foods consumed included waffles with applesauce dipping cup and scrambled eggs with Canadian bacon; scramble with peach cup; quesadilla with pineapple cup; and (testing day): French toast with syrup.; NB: nothing to eat or drink (besides water) until 12pm; Duration: 7d (3-7d washout); Compliance: >90% based on food inventory logs; Outcomes and assessment methods:; - On day 7; - Both groups were given a standardized lunch (500kcal) 5hr after breakfast. Participants were consume ad libitum, at home, throughout the evening. All food items were initially weighed and recorded. The participants were instructed to return all uneaten foods as well as all wrappers and containers from the snacks that were consumed. Any partially eaten, returned items were weighed accordingly to calculate free-living energy intake. | [underlined: Enerqv intake (kcal)], Mean (SEM); In the evening; NB:2252 (366); Breakfast: 1938 (263); p=NS; Total including breakfast and lunch; NB: 2768 (365.5); Breakfast: 2798 (262.9); p=NS | Limitations:; - Methods for randomization and concealment NR; - High attrition and did not account for the impact of those lost to follow-up; - Water/Beverages were not accounted for in exposure assessment; Funding:; Egg Nutrition Center
Halsey, 2012^18^; RCT-Crossover, UK; Baseline N=49, Analytic N=49 (Attrition: 0%); Study objective: To experimentally compare the effects of eating or skipping breakfast on energy expenditure, activity levels and dietary habits.; Participant characteristics at baseline: young adults; - Age: 22.6 (3.9)y; - Female: 53%; - Race and/or ethnicity: NR; - Socio-economic position: 65% were university students; - Anthropometry: NR; - Physical activity: levels of activity: 22% low, 44% moderate, 34% high; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: eat breakfast 5x/wk; Excluded from study or analysis: illness or medical condition that would affect participation in the study | Intervention: Breakfast vs No Breakfast (NB); Breakfast: ad libitum high-carbohydrate breakfast cereals with milk, and/or toast with butter and/or jam if requested ingested between 8-9:15am; participants were provided with breakfast ad libitum in addition to water, tea, or coffee; NB: no breakfast was provided but water, tea, or coffee was offered; Duration: 1wk (consecutive, no washout); Compliance: NR; Outcomes and assessment methods:; - During 1wk intervention; - Energy intake was estimated from 3 consecutive days of food diaries. Participants were asked to record everything they ate and drank from the moment they woke to when they went to bed. Energy intake per day, and from noon until the end of the day, was averaged within participant and condition. | [underlined: Enerqv intake (kcal)], Mean (SEM); Males; NB: 1796 (88); Breakfast: 1987 (107); p=0.127; Females; NB: 1800 (128); Breakfast: 1859 (98); p=0.567 | Limitations:; - Methods for randomization and concealment NR; - Potential bias from period and carryover effects; - Unclear if outcome assessors were aware of intervention assignment; - No power calculation; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; Funding:; Roehampton University
LeCheminant, 2017^19^; RCT-Parallel, U.S.; Baseline N=54, Analytic N=49 (Attrition: 9%); Study objective: To determine the effects of eating breakfast on energy intake, physical activity, body weight, and body fat in women who are nonhabitual breakfast eaters over a 4wk period; Participant characteristics at baseline: women who are non-habitual breakfast eaters; - Age: ~23y; - Female: 100%; - Race and/or ethnicity: NR; - Socioeconomic position: NR; - Anthropometry: BMI ~22 (3.9) kg/m^2^; - Physical activity: NS between groups; - Smoking: 100% nonsmoker; - TEI: 1843 (495) kcal; - Habitual diet at baseline: All ate breakfast ≤2d/wk (inclusion criteria); Excluded from study or analysis: age <18 or >55y, habitual breakfast eaters (eat breakfast >2d/wk), irregular sleepers (<6h of sleep a night and inconsistent wakeup time) such as night shift workers, not weight stable for 3mo prior to the study, tobacco or alcohol use, current dieting, eating disorders, digestive disorders, medications that alter metabolism, presence of a metabolic disease that affects energy balance (e g., diabetes mellitus, cancers, heart disease, etc.), excessive exercise training (vigorous-intensity activity >4 days/week and 30 min per session), participation in college athletics or any elite sport, inability to exercise at a moderate-intensity level (3.0-6.0 METs) | Intervention: Breakfast vs No Breakfast (NB); Breakfast: participants were required to eat within 1,5hr of waking and had to finish eating breakfast meal (15% total energy intake) by 8:30am. There were no eating or snack restrictions after the breakfast meal.; NB: participants did not consume a snack or meal (with the exception of noncaloric beverages) until after 11:30am. Participants were shown examples of typical breakfasts using pictures but were not instructed to eat particular foods.; Both groups were asked to wake up by Sam.; Duration: 4wk; Compliance: 90% for breakfast group and 98% for NB group; Outcomes and assessment methods:; - At baseline, during 4wk intervention; - Energy intake was calculated from ten 24hr dietary recalls (2 weekdays and 1 weekend day at baseline, and 5 weekdays and 2 weekend days during intervention). Energy intake was averaged over baseline and intervention periods. Food consumption during the day was divided into 4 periods: breakfast (4:30-11:3am), lunch (11:30am-4:30pm), dinner (4:30-10 30pm). night eating (10:30pm-4:30am). Food consumption during these times was summed and averaged over 7d. | [underlined: Energy intake (kcal),] Mean (SD); Breakfast (4:30-11:30am); Within group: baseline, during 4wk; NB:66.8 (123.9), 3.02 (14.5); Breakfast: 98.6 (128.2), 424.3 (135.0), p<0.05; Between group: p≤0.05 during 4wk interaction; p-interaction<0.01; Lunch (11:30am-4:30pm); Within group: baseline, during 4wk intervention; NB: 664.6 (276.0), 701.1 (289.0), p=NS; Breakfast: 831.6 (273.3), 774.5 (280.2), p=NS; Between group: p=NS at baseline and during 4wk interaction; p-interaction=0.11; Dinner (4:30-10:30pm); Within group: baseline, during 4wk intervention; NB: 695.7 (329.2), 836.7 (304.9), p=NS; Breakfast: 840.5 (396.0), 746.0 (254.5), p=NS; Between group: p=NS at baseline and during 4wk interaction; p-interaction=0.39; Night eating (10:30pm-4:30am); Within group: baseline, during 4wk intervention; NB: 104.7 (146.9), 79.8 (115.7), p=NS; Breakfast: 112 3 (191.0), 88.0 (113.6), p=NS; Between group: p=NS at baseline and during 4wk interaction; p-interaction=0.76; Total; Within group: baseline, during 4wk intervention; NB: 1696 (407), 1685 (459), p=NS; Breakfast: 1689 (505), 1952 (464), p<0.01; Between group: p=NS at baseline NB<Breakfast during 4wk intervention:; p=0.05; p-interaction=0.01 | Limitations:; - Methods for randomization and concealment NR; - No pre registered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; Funding:; Brigham Young University
Leidy, 2013^21^; RCT-Crossover, U.S.; Baseline N=22, Analytic N=20 (Attrition: 9%); Study objective: To examine whether a high-protein breakfast leads to daily improvements in appetite control, satiety, food motivation/reward, and evening snacking compared with normal protein ready-to-eat cereal breakfast meals in breakfast skipping teenage girls with overweight or obesity; Participant characteristics at baseline: Breakfast-skipping young adult women with overweight and obesity; - Age: 19 (1)y; - Female: 100% - Race and/or ethnicity: NR; - Socioeconomic position: NR; - Anthropometry: BMI 28.6 (0.7) kg/m2; - Physical activity: NR; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: Skips; Breakfast: Mean (SEM), 6 (1) d/wk; Excluded from study or analysis: age <15 or >20y; BMI <25 or >35 kg/m2; metabolic or neurologic diseases or other health complications; taking medications that would influence food intake regulation, appetite, or metabolism; clinically diagnosed with an eating disorder; currently or previously (within the past 6 mo) on a weight-loss or other special diet, pregnant; frequent breakfast eating habits (i.e., >2 breakfast occasions/wk as assessed from a 7-d screening breakfast questionnaire); left-handed (for consistency with the fMRI neural responses). | Intervention: High protein breakfast vs. Normal protein breakfast vs. No Breakfast (NB); Participants were either served a high protein breakfast (HP; egg and beef-rich; 35g protein), normal protein breakfast (NP; ready-to-eat-cereal-based; 13g protein), or continued breakfast skipping (No breakfast). The NB group continued their habitual practice of skipping breakfast for 6d. The NP and HP groups were provided with specific breakfast meals and asked to consume these at home (before school) between 7-9:30am for 6d. All participants were permitted to eat ad libitum throughout the remainder of each day. On day 7, all participants reported to the lab between 6-8am. The NP and HP groups consumed their breakfast meals (including 240 ml_ water) and the NB group drank 240 mL water only; all participants consumed the meal and/or water within 30 minutes.; NP and HP breakfast were matched for energy (~350 kcal), fat content, energy density, dietary fiber, sugar content, dairy and plant protein qualities, and palatability; Duration: 7 consecutive days (≥1wk washout); Compliance: 100% on testing days and 99% during the 6 acclimation days based on daily check-off logs indicating consumption; Outcomes and assessment methods:; - On day 7; - Participants were given dinner at 5pm to eat ad libitum After dinner, participants were given a cooler containing various snacks to consume ad libitum, at home, throughout [he evening; the cooler contained a total of 4000 kcal. All food items were initially recorded and weighed. The participants were instructed to return all uneaten foods as well as all wrappers and containers from [he snacks that were consumed. Any partially eaten, returned items were weighed accordingly. Total energy intake during dinner and from evening snacks was determined from the recorded weights. | [underlined: Energy intake (kcal)], Mean (SEM); At dinner; NB: 845 (60); NP-breakfast: 820 (71); HP-breakfast: 787 (50); p=NS; From evening snacking; NB: 656 (108); NP-breakfast: 621 (110); HP-breakfast: 486 (84); NB vs NP-breakfast: p=NS; NB vs HP-breakfast: p<0.05; Total including breakfast; NB: 2002 (111); NP-breakfast: 2292 (115); HP-breakfast: 2123 (71); NB vs NP-breakfast: p<0.003; NB vs HP-breakfast: p=NS | Limitations:; - Methods for randomization and concealment NR; Funding:; The Beef Check-off; Egg Nutrition Center/American Egg Board
Leidy, 2015^20^; RCT-Parallel, U.S.; Baseline N=67, Analytic N=54 (Attrition: 19%); Study objective: To evaluate whether longer-term consumption of normal-protein vs. high-protein breakfast meals improves appetite control, food intake, and body composition in “breakfast skipping” young people with overweight/obesity; Participant characteristics at baseline: Breakfast-skipping young adults with overweight and obesity; - Age: 19 (1)y; - Female: 59%; - Race and/or ethnicity: Caucasian: 61%: African American: 35%; Other: 4%; - Socioeconomic position: NR; - Anthropometry: BMI ~29 kg/m2; - Physical activity: Examined as potential confounder-NS association with study outcomes; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: Skips; Breakfast: ~6 days/wk; Excluded from study or analysis: age <13 and >20y, BMI <25 and ≥40 kg/m2; those with metabolic diseases/conditions, currently/previously on a weight loss diet; those that do not consistently skip breakfast every weekday | Intervention: High protein breakfast vs. Normal protein breakfast vs. No Breakfast (NB); Participants were either served a high protein breakfast (HP; egg and pork-rich; 35g protein; n-24), normal protein breakfast (NP; ready-to-eat-cereal-based; 13g protein; n=21), or continued breakfast skipping (No breakfast; n=9). The NP and HP groups were provided with specific breakfast meals on a weekly basis with meal preparation instructions and asked to consume these between 6-9:45am. NP and HP breakfast were matched for energy (~1464 kJ) and fat content. The NB group continued their habitual practice of skipping breakfast (nothing to eat or drink besides water) before 10am.; Duration: 12wk; Compliance: Mean 98±1% (NS difference between groups) based on daily check-off logs indicating consumption at the designated times and returned containers of uneaten food; Outcomes and assessment methods:; - At baseline, 12wk follow-up; - Average daily energy intake calculated from three 24hr dietary recalls (2 weekdays and 1 weekend day) | [underlined: Energy intake (kcal), chanqe from baseline to 12wk.] Mean (SEM); NB: +372 (178); NP-breakfast: +118 (51); HP-breakfast: −412 (228); NB vs HP-breakfast: p=0.03; NB vs NP-breakfast: p=NS | Limitations:; - Unclear if outcome assessors were aware of intervention assignment; - No power calculation; - No preregistered data analysis plan; Funding:; Pork Checkoff
Levitsky, 2013^22^; RCT-Crossover, U.S.; Baseline N=24 (sludy 1); 18 (study 2), Analytic N=24 (study 1); 13 (study 2) (Attrition: 0% (study 1); 28% (study 2)); Study objective: The first study examined the effect of skipping breakfast on the amount consumed at lunch. The second study examined the effect of eating a larger breakfast on the amount consumed at lunch and during the rest of the day.; Participant characteristics at baseline: young adults; - Age: Study 1, 22.1 (2.7)y; Study 2, 24.0 (2.8)y; - Female: 80%; - Race and/or ethnicity: NR; - Socioeconomic position: All university students; - Anthropometry: Study 1 BMI, 21 (5.2) kg/m^2^; Study 2 BMI, 24.1 (2.2) kg/m^2^; - Physical activity: NR; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: Regular breakfast eaters: 75% in study 1, 61% in study 2; Excluded from study or analysis: aversions or allergies to foods that would be served; medications (Study 1) | Intervention:; [underlined: STUDY 1]: Hiqh-carbohvdrate breakfast (HC) vs High-fiber breakfast (HF) vs No Breakfast (NB); HC: plain bagel, jelly, orange or apple juice (335 kcal); HF: cereal and 1% milk (338 kcal); NB: no breakfast, unclear if water was allowed; [underlined: STUDY 2]: Breakfast vs No Breakfast (NB); Breakfast served ad libitum, buffet-style (cereal, milk, juice, bagel w CC, jelly, coffee).; Duration: 1d (1wk washout); Compliance: NR; Outcomes and assessment methods:; - Same day as intervention; - Study 1: Participants were provided with an ad libitum lunch and the amount of food remaining; - Study 2: Participants ate breakfast and lunch in the lab. Snacks and dinners were eat at home and participants were asked to return uneaten food in order to calculate energy intake. | [underlined: STUDY 1]; [underlined: Enerav intake (kcal)], Mean (SE); At lunch; NB vs HC, p=NS; NB vs HF, p=NS; Breakfast + lunch; NB: 600 (50); HF: 930 (65); HC: 955 (42); NB < HF and HC, both p<0.001; [underlined: STUDY 2]; [underlined: Energy intake (kcal)]; At lunch; NB > Breakfast (data NR, figure only), p=0.04; Mid-afternoon snack, dinner, evening snack; NB vs Breakfast, p-NS for all eating; Total (including breakfast); NB consumed 450 fewer kcal compared to Breakfast group, p<0.01 | Limitations:; - Methods for randomization and concealment NR; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; Funding:; NR
Neumann, 2016^23^; RCT-Parallel, U.S.; Baseline N=40, Analytic N=24 (Attrition: 40%); Study objective: To determine if breakfast macronutrient composition improved TEF and appetite after a 1wk adaptation in young women who habitually skip breakfast.; Participant characteristics at baseline: young women who habitually skip breakfast; - Age: 24.1 (2)y; - Female: 100%; - Race and/or ethnicity: Caucasian: 58%; Black: 13%; Asian: 8%; Indian: 8%; Hispanic: 13%; - Socioeconomic position: NR; - Anthropometry: BMI ~27 kg/m^2^; - Physical activity: Asked to maintain typical levels during intervention; - Smoking: All nonsmokers; - TEI: NR; - Habitual diet at baseline: All skipped breakfast ≥5d/wk (inclusion criteria); Excluded from study or analysis: smoked, had dietary restrictions, were actively trying to lose weight/restricting eating, had lost weight in the last 6mo, were taking medication (excluding hormonal birth control), were athletes or participated in regular physical activity >3 times per week, had any preexisting metabolic conditions (e.g., type 1 or 2 diabetes) that prevented them from consuminq the test breakfasts | Intervention: Protein-based breakfast vs. Carbohydrate-based breakfast vs. No Breakfast (NB); Participants were either served a protein-based breakfast (PRO), carbohydrate-based breakfast (CHO), or continued breakfast skipping (No breakfast). PRO consisted of a breakfast sandwich, Greek yogurt, and 227 mL water. CHO consisted of English muffin, yogurt, cream cheese, and 227 mL water. The NB group continued their habitual practice of skipping breakfast and drank 227 mL water only. The groups were provided with their specific breakfast meals to consume at home for 6d within 2hr of waking and no later than 10am.; CHO and PRO breakfast were matched for energy (~350 kcal), fat, and fiber.; Duration: 1-8d; Compliance: NR; Outcomes and assessment methods:; - 3d out of the 8d intervention (2 weekdays and 1 weekend), specific timing not described; - Total energy intake was assessed using three 24hr diet records (2 weekdays and 1 weekend, including all meals, snacks, and beverages). Results were used to calculate average daily energy intake during the 8d intervention. | Total energy intake (kcal), Mean (SEM); NB: 2009 (193); CHO: 1603 (127); PRO: 2137 (349); p=NS | Limitations:; - Methods for randomization and concealment NR from intended intervention; - Unclear if outcome assessors were aware of intervention assignment; - Timing of outcome assessment unclear and unclear whether occurred at the same time for all; - Not sufficiently powered, and unclear what power calculations were based; - No preregistered data analysis plan; Funding:; Arkansas Biosciences Institute; USDA
Reeves, 2014^24^; RCT-Crossover, UK; Baseline N=37, Analytic N=37 (Attrition: 0%); Study objective: To investigate the effect of breakfast and breakfast omission on food intake and the timing of subsequent food intakes.; Participant characteristics at baseline: adults with normal and overweight; - Age: 29.5 (7.9)y among normal weight and 36 2 (16.3)y among overweight; - Female: 57%; - Race and/or ethnicity: NR; - Socioeconomic position: NR; - Anthropometry: BMI 21.31 (1.79) kg/m^2^ among normal weight and 29.63 (5.32) among overweight (49% normal weight and 51% overweight/obesity); - Physical activity: NR; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: 51% habitually ate breakfast >5 days/wk; 49% habitually ate breakfast ≤2 days/wk; Excluded from study or analysis: dieting, diabetes, symptoms such as dizziness, fainting and blackouts, high blood pressure or cholesterol medication | Intervention: Breakfast vs No Breakfast (NB); Breakfast: participants were requested to eat breakfast within 1hr of waking; NB: participants were asked to refrain from eating until midday (unclear if water was allowed); Participants were not instructed to eat particular foods.; Duration: 1wk (≥1wk washout); Compliance: NR; Outcomes and assessment methods:; - During 1wk intervention; - Energy intake was estimated from 7 days of food diaries. Participants were asked to record everything they ate and drank from the moment they woke to when they went to bed. Energy intake was also analyzed by four 3hr periods (12-3pm, 3-6pm, 6-9pm, 9pm-12am). | [underlined: Enerqv intake (kcal)], Mean (SD); 12-3pm; NB > Breakfast, p=0.009; p-interaction (BMI)=0.26; 3-6pm; NB: 267 (160); Breakfast: 208 (138); p=0.043; p-interaction (BMI)>0.15; 6-9pm; NB vs Breakfast: p>0.20; Overweight: 637 (219); Normal weight: 450 (162); p-interaction (BMI)<0.0005; 9pm-12am; NB vs Breakfast: p>0.35; p-interaction (BMI)>0.35; Total (12pm-12am); NB: 1787 (516); Breakfast: 1948 (488); p=0.03; p-interaction (BMI)>0.50 | Limitations:; - Methods for randomization and concealment NR; - Unclear if outcome assessors were aware of intervention assignment; - No power calculation; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure; Funding:; Kellogg’s Ltd
Rosi, 2018^25^; RCT-Crossover, Italy; Baseline N=15, Analytic N=15 (Attrition: 0%); Study objective: To investigate the effect of nutritional and cognitive-perceived characteristics of breakfast on metabolic and behavioral variables related to food intake; Participant characteristics at baseline: male habitual breakfast eaters; - Age: 24 (2)y; - Female: 0%; - Race and/or ethnicity: NR; - Socioeconomic position: NR; - Anthropometry: BMI 23.4 (1.6) kg/m^2^; - Physical activity: All moderately active (inclusion criteria); - Smoking: All nonsmokers; - TEI: NR; - Habitual diet at baseline: All eat breakfast daily (inclusion criteria); Excluded from study or analysis: aged <18 and >30y, BMI <20 and >25 kg/m^2^, unstable body weight (>±5% change in 3mo before study), smokers, taking medication, breakfast skippers, following a specific diet, known food allergy | Intervention: Breakfast (Bread) Vs. Breakfast (Muesli) vs. Breakfast (Rice) vs No Breakfast (NB); Breakfast-Bread (B-Bread): white bread with chocolate hazelnut spread; Breakfast-Muesli (B-Muesli): muesli with dark chocolate chips and nuts; Breakfast-Rice (B-Rice): chocolate-flavored puffed rice; NB: 125ml_ decaffeinated tea (0 kcal); Breakfast meals were iso-energetic and similar for protein content.; Duration: 1wk (≥1wk washout); Compliance: NR; Outcomes and assessment methods:; - Same day as intervention and over 1wk; - Participants were provided with an ad libitum lunch, which was double weighed before and after to measure energy intake during lunch. Participants completed a 7d weighed food diary to calculate daily energy intake over the week (as total intake and intake the rest of the day after breakfast). | [underlined: Energy intake (kcal), Mean (SEM)]; During lunch; NB: 2043 (156); B-Bread 1762 (149); B-Muesli: 1705 (85); B-Rice: 1879 (113); p=NS; After breakfast; NB: 2712 (199); B-Bread: 2473 (130); B-Muesli: 2379 (156); B-Rice: 2376 (157); NB vs B-Bread: p=NS; NB> B-Muesli: p=0.023; NB > B-Rice: p=0.029; Total including breakfast; NB: 2712 (199); B-Bread: 2806 (130); B-Muesli: 2707 (156); B-Rice: 2706 (157); p=NS | Limitations:; - Water/Beverages were not accounted for in exposure assessment; Funding:; “Soremartec Italia Sri” (Alba, Cuneo, Italy)
Slater, 2022^26^; RCT-Crossover, UK; Baseline N=14, Analytic N=14 (Attrition: 0%); Study objective: To examine the effects of a very-low-energy, viscous placebo breakfast on subjective appetite, peripheral appetite-regulatory hormone concentrations, and subsequent energy intake at an ad libitum lunch, compared to a typical whole-food breakfast and a water-only control.; Participant characteristics at baseline: male habitual breakfast eaters; - Age. 24 (2)y; - Female: 0%; - Race and/or ethnicity: NR; - Socioeconomic position: NR; - Anthropometry: BMI 23.5 (2.3) kg/m^2^; - Physical activity: NR; - Smoking: All nonsmokers; - TEI: NR; - Habitual diet at baseline: All “regularly consumed breakfast” (inclusion criteria); Excluded from study or analysis: smokers; habitual breakfast skippers; exhibited restrained, disinhibited, or hungry eating tendencies | Intervention: Breakfast vs Placebo Breakfast (PB) vs No Breakfast (NB); Breakfast: typical whole-food breakfast (cereal, milk, bread, jam, apple juice); 20% of EER, 573+30 kcal; PB: viscous breakfast meal (low-calorie flavored squash, xantham gum, and water); equating to 5 mL/kg body mass, 16±1 kcal; NB: water-only control; All groups consumed the same volume of water (618±54mL); Duration: 1d (4d washout); Compliance: adherence with standardization measures were confirmed verbally before each experimental trial; Outcomes and assessment methods:; - Same day as intervention; - Participants were provided with an ad libitum lunch and water intake for 20min. Food and water were weighed before and after to quantify intakes. | [underlined: Energy intake (kcal)]. Mean (SD); During lunch; NB: 1093 (249); PB: 1062 (273); Breakfast: 981 (284); NB vs PB, p=1.000; NB > Breakfast, p<0.05; PB vs Breakfast, p=0.086; Breakfast + lunch; NB: 1093 (249); PB: 1078 (274); Breakfast: 1554 (301); NB vs PB, p=1.000; NB < Breakfast, p<0.001; PB < Breakfast, p<0.001 | Limitations:; - No preregistered data analysis plan; Funding:; Nottingham Trent University
Thomas, 2015^27^; RCT-Crossover, U.S.; Baseline N=24, Analytic N=17 (Attrition: 29%); Study objective: To investigate the metabolic and appetitive responses to skipping breakfast in overweight women who were habitual breakfast Eaters or Skippers.; Participant characteristics at baseline: Women with overweight; - Age: 29 (27-32)y; - Female: 100%; - Race and/or ethnicity: Caucasian: 72%; African American: 22%; Asian: 6%; Non-Hispanic: 88%; - Socioeconomic position: NR; - Anthropometry: BMI 30.2 (28.6-33 7) kg/m^2^; - Physical activity: NR; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: 50% ate breakfast <2d/wk; Excluded from study or analysis: aged <25 or >40y, BMI <27 or >35 kg/m^2^, eating disorders, women without menses, night eating syndrome, active dieting or intensive exercise training | Intervention: Breakfast vs No Breakfast (NB); Breakfast: 250mL water + breakfast meal containing 25% of total daily energy intake (cereal, milk, eggs, orange juice) consumed within 20min; NB: 250mL water; Duration: 1d (1mo washout); Compliance: 1 participant did not follow protocol; Outcomes and assessment methods:; - Same day as intervention; - All participants were provided with a standard lunch 4hr after breakfast; lunch contained 35% of daily energy intake and they had 20min to consume. Participants were provided with an ad libitum dinner (2600 kcal) 5hr after lunch and intake was determined by weigh-back methods. Participants were provided with a box of snack foods to take home and uneaten portions were returned the following day to calculate energy intake. | Enerqv intake (kcal). Median (IQR); At dinner; NB: 837 (594-972); Breakfast: 815 (550-1072); p=NS; During evening snack; NB: 716 (360-1197); Breakfast: 701 (177-1023); p=NS; Total including breakfast and lunch; NB: 2344 (1913-2777); Breakfast: 2516 (2363-3324); p=NS | Limitations:; - No power calculation; - No preregistered data analysis plan; Funding:; NIH; Nutrition Obesity Research Center
Veasey, 2015^28^; RCT-Crossover, UK; Baseline N=25, Analytic N=22 (Attrition: 12%); Study objective: To compare the effects of two different sized breakfasts and no breakfast consumed prior to morning exercise on cognitive function, mood, appetite and energy intake for the remainder of the day; Participant characteristics at baseline: habitually active females; - Age 20.9 (2.3)y; - Female: 100%; - Race and/or ethnicity: NR; - Socioeconomic position: NR; - Anthropometry: BMI 21.9 (1.9) kg/m^2^; - Physical activity: All exercised for ≥30min 3x/wk during the previous 6mo (inclusion criteria); - Smoking: All nonsmokers; - TEI: NR; - Habitual diet at baseline: All habitually consumed breakfast; Excluded from study or analysis: age <18 or >35y; smoker; taking medication or herbal and dietary supplements; history of head trauma, learning difficulties, attention deficit hyperactivity disorder, dyslexia, migraines or gastric problems; BMI <18 or >25 kg/m^2^; blood pressure >140/90 mmHg; not habitually active and did not regularly exercise in the morning, unable to run for 30min continuously at a moderate speed, habitually skipped breakfast prior to a morning exercise session | Intervention: Breakfast (20g) vs. Breakfast (40g) vs No Breakfast (NB); 20g Breakfast (20g): 20g cereal + 83mL milk (118 kcal total), consumed within 10 minutes; 40g Breakfast (40g): 40g cereal + 166 mL milk (236 kcal total), consumed within 10 minutes; NB: no breakfast (unclear if water was allowed); Duration: Id (≥2d washout); Compliance: NR; Outcomes and assessment methods:; - Same day as intervention; - Participants were provided with an ad libitum pasta lunch in pre-weighed servings in order to calculate energy intake at lunch. Participants completed a food diary for the rest of the day, which was used to estimate food intake after lunch. | [underlined: Energy intake (kcal)], Mean (SEM); Ad-libitum lunch; NB: 763.2 (37.2); 20g: 786.2 (37.1); 40g: 778.7 (38.8); p=NS; Self-reported intake after lunch; NB: 1000.8 (76.9); 20g: 1055.9 (105.6); 40g: 1067.5 (114.5); p=NS; Total (breakfast, lunch, after lunch); NB: 1780.14 (80.59); 20g: 1957.21 (114.64); 40g: 2088.57 (132.30); P=NS | Limitations:; - Methods for randomization and concealment NR; - Unclear if outcome assessors were aware of intervention assignment; - Not sufficiently powered; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure; Funding:; Northumbria University
Yoshimura, 2017^29^; RCT-Crossover, Japan; Baseline N=20, Analytic N=20 (Attrition: 0%); Study objective: To evaluate the acute effects of skipping breakfast on energy intake and physical activity under free-living conditions among healthy lean women who are habitual breakfast eaters; Participant characteristics at baseline: healthy, lean women - Age 21.8 (0.9)y; - Female: 100%; - Race and/or ethnicity: NR; - Socioeconomic position: All were university students; - Anthropometry: Mean BMI: 20.2 kg/m^2^; - Physical activity: NR; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: All eat breakfast ≥5 times/wk (inclusion criteria); Excluded from study or analysis: aged >21 or >25y, BMI <17.3 or >24.2 kg/m^2^, metabolic disorders, habitual breakfast skippers (≥2d/wk) | Intervention: Breakfast vs No Breakfast (NB); Breakfast: at 8am, participants ate rice, ham, eggs, and salad (30% of total daily energy), and 500 mL of water and were asked to consume the meal within 20 minutes; NB: 500 mL of water; Duration: 1d (2.3±0.7d washout); Compliance: NR; Outcomes and assessment methods:; - Same day as intervention; - Energy intake was evaluated by adding values from food labels of purchased food (participants were instructed to eat all purchased food). Meals were photographed to confirm contents. The meal was divided into 4 categories by eating time (lunch, mid-afternoon snack, dinner, evening snack) The meal between lunch and dinner was defined as a mid-afternoon snack; the meal after dinner was defined as an evening snack. | [underlined: Energy intake (kcal)], Mean (SD); At lunch; NB: 780 (140); Breakfast: 649 (166); p=0.0057; At mid-afternoon snack, dinner, or evening snack; NB vs Breakfast (data NR, figure only): p=NS for all eating occasions; Total excluding breakfast; NB: 1853 (410); Breakfast: 1573 (348); p=0.009; Total including breakfast; NB: 1853 (410); Breakfast: 2215 (348); p=0.013 | Limitations:; - No power calculation; Funding:; Yazuya Co., Ltd.
PROSPECTIVE COHORT STUDY
[underlined: Zhang. 2017]^30^; PCS, Secondary analysis of an RCT comparing AHA diet to high-fiber diet, U.S.; Analytic N=178; Study objective: To examine the association between breakfast skipping and body weight, nutrient intake, and metabolic parameters in participants with metabolic syndrome; Participant characteristics at baseline: adults with MetS; - Age: 52.2y; - Female: 73%; - Race and/or ethnicity: White: 88%; Other: 12%; - Socioeconomic position: Education: 75% Bachelor’s degree or less; 25% Graduate/professional; Household income: 27% <$50k, 50% ≥$50,001, 23% unclear; 79% employed full-time or part-time; - Anthropometry: 48% BMI 30-34.9 and 52% BMI 35-40 kg/m^2^; - Physical activity: Mean duration of total physical activity 235 min/wk in NB group vs 200 min/wk in Breakfast group, p=0.02; - Smoking: All nonsmokers; - TEI: Breakfast: 1984 kcal/d vs NB: 1816 kcal/d; p=0.05; - Habitual diet at baseline: 33% skipped breakfast, 33% ate breakfast daily; Excluded from study or analysis: age <21 and >70y; BMI <30 and >40 kg/m^2^; smokers; no diagnosis of MetS; clinically diagnosed diabetes or fasting blood sugar levels 2126 mg/dL, an acute coronary event within last 6mo, pregnant or lactating, PCOS, intention to move out of the area within 1yr study period, current participation in a weight loss program, an eating disorder, bariatric surgery, elevated depression or suicidal ideation, or subjects following a low-carbohydrate, high fat dietary reqimen. | Exposure: Breakfast vs No Breakfast (NB); Participants who reported eating breakfast at least once were considered breakfast eaters and those who did not consume any breakfast on the three dietary recall days were categorized as breakfast skippers. Breakfast included consumption of any food/beverage (excluding water) at the first eating episode no later than 10am.; Assessment methods and timing:; - Self-reported using three unannounced 24hr diet recalls; - At baseline; Outcomes and assessment methods:; - At baseline, 1yr follow-up; Total energy intake assessed by three 24hr dietary recalls | [underlined: Change in total enerqv intake (kcal) over] [underlined: 1yr], Mean (95% Cl); NB: −133.9 (−365.1, 97.4); Breakfast: −260.7 (−398.1, −123.3); p=0.23 | Model adjustments:; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, physical activity, smoking; - Other: group; Limitations:; - Did not account for key confounders: anthropometry; - Exposure assessment method not validated and exposure data only assessed at baseline leading to a concern that changes in exposure status occurred over 1yr f/u; - No information on non-completers; - No pre registered data analysis plan; Funding:; NHLBI; China Scholarship Council

a Abbreviations: B: breakfast; BMI: body mass index; BE: breakfast-exercise; BR: breakfast-rest; CHO: carbohydrate-based; CON: control; d: day; EI: energy intake; EX: exercise; HC: high carbohydrate; HF: high fat; HP: high protein; kcal: kilocalories; MJ: megajoule; MVPA: moderate to vigorous physical activity; NB: no breakfast; NBE: no breakfast-exercise; NBR: no breakfast-rest; NP: normal protein; NR: not reported; NS: not significant; PRO: protein-based; SE: standard error; SD: standard deviation; SN: snack; TEI: total energy intake; wk: week(s); y: year(s)

Table 11 Risk of bias for randomized controlled trials examining breakfast consumption in adults and energy intake^a^

Article | Randomization | Period and carryover effects | Deviations from intended interventions | Missing outcome data | Outcome measurement | Selection of reported result | Overall risk of bias
Astbury, 2011 ^6^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Betts, 2014 ^7^ | LOW | NOT APPLICABLE | LOW | LOW | LOW | LOW | LOW
Chowdhury, 2015 ^10^ | SOME CONCERNS | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Chowdhury, 2016a ^9^ | LOW | NOT APPLICABLE | LOW | LOW | LOW | LOW | LOW
Chowdhury, 2016b ^11^ | SOME CONCERNS | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Chowdhury, 2018 ^12^ | LOW | NOT APPLICABLE | LOW | LOW | LOW | LOW | LOW
Chowdhury, 2019 ^8^ | LOW | NOT APPLICABLE | LOW | LOW | LOW | LOW | LOW
Clayton, 2015 ^13^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Edinburgh, 2019 ^14^ | LOW | LOW | LOW | LOW | LOW | LOW | LOW
Farshchi, 2005a ^15^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS
Gonzales, 2013 ^16^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Griffiths, 2020 ^17^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Gwin, 2018 ^31^ | SOME CONCERNS | SOME CONCERNS | LOW | HIGH | LOW | LOW | HIGH
Halsey, 2012 ^18^ | SOME CONCERNS | HIGH | LOW | LOW | SOME CONCERNS | SOME CONCERNS | HIGH
LeCheminant, 2017 ^19^ | SOME CONCERNS | NOT APPLICABLE | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Leidy, 2013 ^21^ | SOME CONCERNS | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Leidy 2015 ^20^ | SOME CONCERNS | NOT APPLICABLE | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Levitsky, 2013 ^22^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Neumann, 2016 ^23^ | SOME CONCERNS | NOT APPLICABLE | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS
Reeves, 2014 ^24^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS
Rosi, 2018 ^25^ | LOW | LOW | LOW | LOW | LOW | LOW | LOW
Slater, 2022 ^26^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Thomas, 2015 ^27^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Veasey, 2015 ^28^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS
Yoshimura, 2017 ^29^ | LOW | LOW | LOW | LOW | LOW | LOW | LOW

a Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898. doi:10.1136/bmj.l4898 31462531 .)

Table 12 Risk of bias for observational study examining breakfast in adults and energy intake^b^

| Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of reported result | Overall risk of bias
Zhang, 2017^30^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH

b Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the “Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)” tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602 .)

Table 13 Evidence examining the relationship between number of eating occasions in adults and energy intake^a^

Study and Population Characteristics | Intervention, Comparator, and Outcome(s) | Results | Study Limitations
RANDOMIZED CONTROLLED TRIALS
Bachman, 2012^32^; RCT-Parallel, Lifestyle, Eating, and Activity Patterns (LEAP), U.S.; Baseline N=51, Analytic N=51 (Attrition: 0%); Study objective: To examine the effect of eating frequency on hunger, energy intake, and weight loss during a 6-month behavioral weight loss intervention; Participant characteristics at baseline: adults with overweight/obesity participating in a 6mo behavioral weight loss intervention; - Age: 51 (9.9)y; - Female: 58%; - Race and/or ethnicity: White: 94%; Black: 6%; Asian: 0%; American Indian: 0%; Other: 0%; non-Hispanic: 98%; - Socioeconomic position: Education: 8% high school, 4% vocational school, 31% some college, 31% college graduate, 26% graduate school; 78% married; 12% divorced/separated; - Anthropometry: BMI 35.5 kg/m^2^ (100% with overweight or obesity); - Physical activity: ~800 kcal/wk expended; - Smoking: NR; - TEI: ~2200 kcal/d; - Habitual diet at baseline: ~4 eating bouts/d (~2.8 meals, 1.2 snacks); Excluded from study or analysis: age <21 and >65y; BMI <27 and >45 kg/m^2^, reported a heart condition; chest pain or loss of consciousness during activity, unable to walk 2 blocks without stopping, major psychological disease; diabetes; recent weight loss or in a weight loss program; moving outside the area; pregnant, lactating, <6mo postpartum, or planned to become pregnant; unwilling to complete study meetings, assessments, or food diaries for duration of study | Intervention: 6 vs 3 meals per day (hypocaloric); 6 Meal Group (n=26): Instructions to “graze” by eating at least 100 kcal every 2-3hr + standard behavioral intervention for obesity for 6mo (~6 eating bouts/d at 3 and 6mo, 3 meals and 3 snacks); 3 Meal Group (n=25): Instructions to eat 3 meals/d + standard behavioral intervention for obesity for 6mo (−3 eating bouts/d at 3 and 6mo, all 3 meals); Participants defined meals and snacks, which were only counted if at least 25kcal were consumed. All foods and beverages eaten within ½hr of the start of a meal/snack were counted as a single eating bout. Eating frequency equaled the number of meals, snacks, and total eating bouts (meals + snacks) reported in the food records.; Duration: 6mo; Compliance: Based on percent of self-monitoring diaries turned in and attendance for each participant. NS difference between conditions for self-monitoring, attendance, and retention at 3 or 6 month assessments.; Outcomes and assessment methods:; - At baseline, 3mo, and 6mo; - Overall energy intake was assessed by 3 day (2 weekdays, 1 weekend) dietary records. Each food record was entered into NDSR and mean intake of overall energy intake over the 3 days was calculated. | [underlined: Total daily energy intake (kcal)], Mean (SD); Within group: 0mo, 3mo, 6mo, p<0.001; 3 Meals: 2142 (727), 1111 (249), 1217 (354), p<0.001; 6 Meals: 2252 (667), 1280 (210), 1314 (352), p<0.001; Between groups: p=NS at 0, 3, 6mo | Limitations:; - Water was not accounted for in exposure assessment; Funding:; American Heart Association
Forslund, 2008^33^; RCT-Parallel, Sweden; Baseline N=140, Analytic N=93 (Attrition: 34%); Study objective: To examine the effect of two different recommended eating frequencies on 1-year weight loss; Participant characteristics at baseline: adults with obesity; - Age:~41 (11)y; - Female: 71%; - Race and/or ethnicity: NR; - Socioeconomic position: NR; - Anthropometry: All with BMI >30 kg/m^2^; - Physical activity: NR; - Smoking: NR; - TEI:~2700 kcal/d; - Habitual diet at baseline: NR; Excluded from study or analysis: aged <18 or >60y; BMI <30 kg/m^2^; participants reporting previous obesity surgery, anti-obesity drug treatment the last year, drug or insulin-treated diabetes, hypothyroidism, severe psychiatric disorder, bulimia, drug or alcohol abuse | Intervention: 6 vs 3 meals per day (hypocaloric); 6 meals a day (6M, n=44): daily energy intake divided into breakfast (20%), lunch (25%), dinner (25%) and 3 snacks (10% each).; 3 meals a day (3M, n=46): daily energy intake divided in breakfast (30%), lunch (35%) and dinner (35%). No snacks with the exception of limited fruit intake and calorie-free drinks.; Duration: 1yr; Compliance: Measured using repeated telephone intervals at 6 time periods during the 1 yr intervention; Outcomes and assessment methods:; - At baseline, 1yr; - Energy intake assessed using self-administered dietary questionnaire on habitual intake during the past 3mo | [underlined: Total daily enerqv intake (kcal).] Mean (SD); Total Sample; Within group: baseline, 1yr; 3 Meals: 2805 (1230), 2098 (609), p<0.001; 6 Meals: 2652 (910), 2150 (877), p<0.01; Between group: difference in change from baseline to 1yr; 95% Cl for difference between changes: (−746, 375), p=0.51; [underlined: Change from baseline to 1vr (kcal)]; Men; 3 Meals: 991; 6 Meals: 484; Woman:; 3 Meals: 618; 6 Meals: 544 | Limitations:; - Concerns with deviations from intended intervention; - High rates of attrition, and unclear how missing data impacted results; - Not sufficiently powered; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure; Funding:; Vastra Gotalandsregionen
Grangeiro, 2021^34^; RCT-Parallel, Brazil; Baseline N=47, Analytic N=40 (Attrition: 15%); Study objective: To examine the effect of different meal frequencies on weight loss, body composition, blood glucose, plasma lipids, active ghrelin, and energy expenditure outcomes among women with obesity who had enrolled in a weight loss intervention.; Participant characteristics at baseline: women with obesity enrolled in a weight loss intervention; - Age: Mean ~30y; - Female: 100%; - Race and/or ethnicity: NR; - Socioeconomic position: NR; - Anthropometry: BMI ~35 kg/m2; - Physical activity: Asked to maintain physical activity during intervention; - Smoking: Ail nonsmokers; - TEI:~1900 kcal/d; - Habitual diet at baseline: NR; Excluded from study or analysis: 8MI <30 and ≥50 kg/m^2^, aged <20 or >45y, menopausal, smokers, with restricted diets, with recent changes in body weight (±3 kg in the previous three months), undergone bariatric surgery, athletes, users of medication or supplements for weight control, people diagnosed with acute or chronic disease, (e g., decompensated hypothyroidism, diabetes, respiratory complications, cancer, inflammatory bowel disease, liver and severe kidney diseases, and heart disease), dyslipidemia, illiterate, those with severe food compulsion at baseline (based on Binge Eating Scale) | Intervention: 6 vs 3 meals a day (hypocaloric); The 6-meal group was a hypocaloric diet divided into breakfast (15% TEE), snack (5-10% TEE), lunch (25% TEE), snack (5-10% TEE), dinner (25% TEE) and evening snack (5-10% TEE).; The 3-meal group was a hypocaloric diet divided into breakfast (20-25% TEE), lunch (35-40% TEE), and dinner (35-40% TEE).; The diets had the same macronutrient distribution. Diets were reduced 500-1000 kcal/d to obtain body weight reduction of 2-4 kg/mo. Breakfast, lunch and dinner were defined to provide more than 15% of the TEE and the snacks provided less than 15% of the TEE.; Duration: 12wk; Compliance: Self-reported dietary adherence: NS difference between groups; percentage (~75%) remained similar throughout intervention period; Outcomes and assessment methods:; - At baseline, 12wk; - Energy intake measured from self-reported food records that were conducted at three periodic visits during the 12wk intervention | [underlined: Total daily energy intake (kcal),] Marginal mean (SD); Within group: baseline, 12wk; 3-meal: 1973.91 (86.73), 1530.00 (104.88), p=0.0106; 6-meal: 1892.13 (79.65), 1292.06 (111.34), p=0.001; Between groups:; p=0.888 at baseline; p=0.544 at 12wk; [underlined: Change in energy intake (kcal) from baseline to 12wk], Marginal mean (SD); 3-meal: −356.84 (157.58); 6-meal:-733.19 (171.07); p=0.216 | Limitations:; - Methods for concealment NR; - Concerns with deviations from intended intervention; - Differences in attrition; - Water/Beverages were not accounted for in exposure; Funding:; Coordenaçao de Aperfeiçoamento de Pessoal de Nível Superior (CAPES)
Meessen, 2022^36^; RCT-Crossover, Norway; Baseline N=13, Analytic N=11 (Attrition: 15%); Study objective: To investigate the physiological effects of eucaloric time-restricted eating (22/2, one meal per day in the evening) for 11 days on metabolic health and physical performance in free-living healthy lean individuals compared to normal food intake (three meals per day) in a crossover design.; Participant characteristics at baseline: lean adults; - Age: 31.0 (1.7)y; - Female: 55%; - Race and/or ethnicity: NR; - Socioeconomic position: NR; - Anthropometry: BMI 24.0 (0.6) kg/m2; fat mass 24.0 (0.6)%; - Physical activity: All with training experience in order to perform physical performance tests (inclusion criteria); - Smoking: All nonsmokers; - TEI: NR; - Habitual diet at baseline: NR; Excluded from study or analysis: BMI <20 or >30 kg/m2; fat mass <12 or >30%; no training experience; history of cardiovascular disease, diabetes mellitus (type 1 or type 2), eating disorders, mental disorders, other diseases which may affect metabolism; cholecystectomy; smoking, already on an intermittent fasting pattern (self-reported) | Intervention: 3 vs 1 meals per day (eucaloric); 3 eating occasions: participants ate 3 meals a day (breakfast, lunch, dinner); 1 eating occasion: participants ate 1 meal a day between 5-7pm; Participants consumed individually designed diets (based on gender, age, weight, height, and activity pattern) in order to maintain a stable weight. Participants were allowed to consume unlimited water, coffee or tea (without sugar/honey). Only artificial sweeteners were allowed.; Duration: 11d (2wk washout); Compliance: NR; Outcomes and assessment methods:; - Day 5, 8, and 11 of the intervention; - Participants completed food diaries, which was used to calculate energy intake. | [underlined: Energy intake (kcal).] Mean (SEM); Day 5; 1 meal: 2342 (233); 3 meals: 2391 (211); p>0.05; Day 8; 1 meal: 2245 (305); 3 meals: 2421 (208); p>0.05; Day 11; 1 meal: 2307 (289); 3 meals: 2404 (248); p>0.05 | Limitations:; - Methods for randomization and concealment NR; - Unclear if outcome assessors were aware of intervention assignment; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; Funding:; ZonMW; Dutch Diabetes Foundation
Papakonstantinou, 2018^37^; RCT-Crossover, Greece; Baseline N=53, Analytic N=47 (Attrition: 11%); Study objective: To evaluate the effects of long-term 6 vs 3 meal eucaloric eating patterns on indices of glycemic control and satiety in subjects with obesity and either IGT or T2D on a weight maintenance diet; Participant characteristics at baseline: adults with impaired glucose tolerance or overt T2D; - Age: 49.3 (1.8)y; - Female: 53% - Race and/or ethnicity: NR; - Sodoeconomic position: NR; - Anthropometry: BMI 32.4 (0.8) kg/m^2^ (all with obesity); - Physical activity: PAL 1.40 (0.03); - Smoking: 19% smokers; - TEI: NR; - Habitual diet at baseline: Adherence to Mediterranean-like dietary pattern (range 0-55): 32.2 (0.6); Excluded from study or analysis: 2hr plasma glucose concentrations ≤ 140 mg/dL after a 75 g oral glucose tolerance test; BMI <30 or >45 kg/m^2^. age <19 or >65y; previous lifestyle modification interventions (structured dietary plans and/or exercise weight loss programs); antidiabetic drug treatment; kidney, liver or cardiovascular disease; hematological abnormalities; hyper- or hypothyroidism; cancer; and mental disorders | Intervention: 6 vs 3 meals a day (eucaloric); Participants followed a weight maintenance diet consumed either as a 3- or 6-meal pattern. Meals were defined as eating occasions providing >150 kcal in the morning (‘breakfast’), at midday (‘lunch’) and in the evening (‘dinner’). Snacks were defined as eating episodes of <150 kcal consumed at times other than specific meal times.; Duration: 12wk (washout NR) Compliance! determined from food records and structured interviews; all participants completed their food diaries; Outcomes and assessment methods:; - Biweekly during the 12wk intervention; - Participants recorded their caloric intake on a daily basis, including the type and amount of any food and beverage consumed throughout the intervention periods There was NS difference between 3- and 7-day food records, so data from 3-day food records (2 consecutive weekdays and 1 weekend day) were used for analysis. | [underlined: Total daily energy intake (kcal) during the 12wk intervention]. Mean (SEM); 3-meals: 1917 (56); 6-meals: 2081 (92); p=0.13 | Limitations:; - Bias arising from carryover effects; - No power calculation; - Water/Beverages were not accounted for in exposure assessment; Funding:; None reported
PROSPECTIVE COHORT STUDIES
Huseinovic, 2021^35^; PCS, Secondary analysis of LEVA (Lifestyle for effective weight loss during lactation) RCT, Sweden; Analytic N=60; Study objective: To examine associations among change in eating frequency and change in energy intake and weight during a 12-week successful weight loss intervention in postpartum women with overweight or obesity; Participant characteristics at baseline: Postpartum women with overweight and obesity undergoing a 12wk weight loss intervention; - Age 33.2<4.1)y; - Female: 100%; - Race and/or ethnicity: NR; - Socioeconomic position: 8% ≤high school; 20% <3y beyond high school; 72% >3y beyond high school; 95% married orcohabitating; 3% single; 2% couple with different residences; - Anthropometry: BMI 30.1 (2.7) kg/m^2^; - Physical activity: NR; - Smoking: NR; - TEI: NR; - Habitual diet at baseline: Mean (SD) 5.9 (1.2) number of eating occasions per day (range 4-10); Excluded from study or analysis: Missing diet record at 12wk | Exposure: Eating frequency defined as the mean number of intake occasions per day. An intake occasion was defined as an energy intake of ≥50 kcal, including foods and/or beverages, separated in time from the preceding and following intake occasion by at least 30 min.; Assessment methods and timing:; - 4d diet record; - At 10-14wk postpartum and 12wk later (post-intervention at 22-26wk postpartum); Outcomes and assessment methods:; - At 10-14wk postpartum and 12wk later (post-intervention at 22-26wk postpartum); - Energy intake calculated from weighed 4d diet records; participants were provided with electronic scale and instructed to register all foods and beverages and weigh to the nearest 1g | [underlined: Chanqe in total daily enerqy intake (kcal) by change in eatinq frequency over 12wk.]; β (SE); 169 (69), p=0.017 | Model adjustments:; - Key confounders: sex, age, socioeconomic position, anthropometry, physical activity; - Other: parity; human milk feeding, dietary treatment (intervention group); eating frequency (for weight analysis); Limitations:; - Did not account for key confounders: race and/or ethnicity, smoking; - Did not describe or; - No preregistered data analysis plan;; - Water/Beverages were not accounted for in exposure; - Did not adjust for TEI; Funding:; Swedish Research Council; Swedish Council for Working Life and Social Research

a Abbreviations: BMI: body mass index; CON: control; d: day(s); EI: energy intake; EX: exercise; g: gram(s); kcal: kilocalories; MJ: megajoule; MVPA: moderate to vigorous physical activity; PCS: prospective cohort study; NB: no breakfast; NR: not reported; NS: not significant; RCT: randomized controlled trial; SD: standard deviation; SE: standard error; SEM: standard error of the mean; SN: snack; TEE: total energy expenditure; TEI: total energy intake; wk: week(s); y: year(s)

Table 14 Risk of bias for randomized controlled trials examining number of eating occasions in adults and energy intake^a^

Article | Randomization | Period and carryover effects | Deviations from intended interventions (effect of assignment) | Missing outcome data | Outcome measurement | Selection of the reported result | Overall risk of bias
Bachman, 2012 ^32^ | LOW | NOT APPLICABLE | LOW | LOW | LOW | LOW | LOW
Forslund, 2008 ^33^ | LOW | NOT APPLICABLE | HIGH | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Grangeiro, 2021 ^34^ | SOME CONCERNS | NOT APPLICABLE | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS
Meessen, 2022 ^36^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS
Papakonstantinou, 2018 ^37^ | LOW | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS

a Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898. doi:10.1136/bmj.l4898 31462531 .)

Table 15 Risk of bias for observational study examining number of eating occasions in adults and energy intake^b^

| Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of reported result | Overall risk of bias
Huseinovic, 2021^35^ | HIGH | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH

b Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the “Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)” tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602 .)

Table 16 Evidence examining the relationship between snacking in adults and energy intake^a^

Study and Population Characteristics | Intervention, Comparator, and Outcome(s) | Results | Study Limitations
Bachman, 2012^32^; RCT-Parallel, Lifestyle, Eating, and Activity Patterns (LEAP), U.S.; Baseline N=51, Analytic N=51 (Attrition: 0%); Study objective: To examine the effect of eating frequency on hunger, energy intake, and weight loss during a 6-month behavioral weight loss intervention; Participant characteristics at baseline: adults with overweight/obesity participating in a 6mo behavioral weight loss intervention; - Age: 51 (9.9)y; - Female: 58%; - Race and/or ethnicity: White: 94%; Black: 6%; Asian: 0%; American Indian: 0%; Other: 0%; non-Hispanic: 98%; - Socioeconomic position: Education: 8% high school, 4% vocational school, 31% some college, 31% college graduate, 26% graduate school; 78% married; 12% divorced/separated; - Anthropometry: BMI 35.5 kg/m^2^ (100% with overweight or obesity); - Physical activity: ~800 kcal/wk expended; - Smoking: NR; - TEI: ~2200 kcal/d; - Habitual diet at baseline: ~4 eating bouts/d (~2.8 meals, 1.2 snacks); Excluded from study or analysis: age <21 and >65y; BMI <27 and >45 kg/m^2^, reported a heart condition; chest pain or loss of consciousness during activity, unable to walk 2 blocks without stopping, major psychological disease; diabetes; recent weight loss or in a weight loss program; moving outside the area; pregnant, lactating, <6mo postpartum, or planned to become pregnant; unwilling to complete study meetings, assessments, or food diaries for duration of study | Intervention: Snacking vs No Snacking (hypocaloric); Snacking (n=25): Instructions to eat 3 meals/d + standard behavioral intervention for obesity for 6mo (~3 eating bouts/d at 3 and 6mo, all 3 meals) No Snacking (Grazing, n=26): Instructions to “graze” by eating at least 100 kcal every 2-3hr + standard behavioral intervention for obesity for 6mo (~6 eating bouts/d at 3 and 6mo, 3 meals and 3 snacks); Participants defined meals and snacks, which were only counted if at least 25kcal were consumed. All foods and beverages eaten within ½hr of the start of a meal/snack were counted as a single eating bout Eating frequency equaled the number of meals, snacks, and total eating bouts (meals + snacks) reported in the food records.; Duration: 6mo; Compliance: Based on percent of self-monitoring diaries turned in and attendance for each participant. NS difference between conditions for self-monitoring, attendance, and retention at 3 or 6 month assessments.; Outcomes and assessment methods:; - At baseline, 3mo, and 6mo; - Overall energy intake was assessed by 3 day (2 weekdays, 1 weekend) dietary records. Each food record was entered into NDSR and mean intake of overall energy intake over the 3 days was calculated. | [underlined: Total daily energy intake (kcal),] Mean (SD); Within group: 0mo, 3mo, 6mo, p<0.001; No Snacking: 2142 (727), 1111 (249), 1217 (354), p<0.001; Snacking: 2252 (667), 1280 (210), 1314 (352), p<0.001; Between groups: p=NS at 0, 3, 6mo | Limitations:; - Water was not accounted for in exposure assessment; Funding:; American Heart Association
Forslund, 2008^33^; RCT-Parallel, Sweden; Baseline N=140, Analytic N=93 (Attrition: 34%); Study objective: To examine the effect of two different recommended eating frequencies on 1-year weight loss; Participant characteristics at baseline: adults with obesity; - Age:~41 (11)y; - Female: 71%; - Race and/or ethnicity: NR; - Socioeconomic position: NR; - Anthropometry: All with BMI >30 kg/m^2^; - Physical activity: NR; - Smoking: NR; - TEI:~2700 kcal/d; - Habitual diet at baseline: NR; Excluded from study or analysis: aged <18 or >60y; BMI <30 kg/m^2^; participants reporting previous obesity surgery, anti-obesity drug treatment the last year, drug or insulin-treated diabetes, hypothyroidism, severe psychiatric disorder, bulimia, drug or alcohol abuse | Intervention: Snacking vs No Snacking (hypocaloric); Snacking: consumed snacks 3x/day (10% of daily energy intake each) in additional to 3 meals; No Snacking: consumed no snacks (with the exception of limited fruit intake and calorie free drinks); Duration: 1yr; Compliance: Measured using repeated telephone intervals at 6 time periods during the 1yr intervention; Outcomes and assessment methods:; - At baseline, 1yr; - Energy intake assessed using self-administered dietary questionnaire on habitual intake during the past 3mo | [underlined: Total daily energy intake (kcal),] Mean (SD); Total Sample; Within group: baseline, 1yr; No Snacking: 2805 (1230), 2098 (609), p<0.001; Snacking: 2652 (910), 2150 (877), p<0.01; Between group: difference in change from baseline to 1yr; 95% Cl for difference between changes: (−746, 375), p=0.51; [underlined: Chanae from baseline to 1vr (kcal)]; Men; No Snacking: 991; Snacking: 484; Women:; No Snacking: 618; Snacking: 544 | Limitations:; - Concerns with deviations from intended intervention; - High rates of attrition, and unclear how missing data impacted results; - Not sufficiently powered; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure; Funding:; Västra Götalandsregionen
Grangeiro, 2021^29^; RCT-Parallel, Brazil; Baseline N=47, Analytic N=40 (Attrition: 15%); Study objective: To examine the effect of different meal frequencies on weight loss, body composition, blood glucose, plasma lipids, active ghrelin, and energy expenditure outcomes among women with obesity who had enrolled in a weight loss intervention.; Participant characteristics at baseline: women with obesity enrolled in a weight loss intervention; - Age: Mean ~30y; - Female: 100%; - Race and/or ethnicity: NR; - Socioeconomic position: NR; - Anthropometry: BMI ~35 kg/m2; - Physical activity: Asked to maintain physical activity during intervention; - Smoking: Ail nonsmokers; - TEI:~1900 kcal/d; - Habitual diet at baseline: NR; Excluded from study or analysis: BMI <30 and ≥ 50 kg/m^2^, aged <20 or >45y, menopausal, smokers, with restricted diets, with recent changes in body weight (±3 kg in the previous three months), undergone bariatric surgery, athletes, users of medication or supplements for weight control, people diagnosed with acute or chronic disease, (e.g., decompensated hypothyroidism, diabetes, respiratory complications, cancer, inflammatory bowel disease, liver and severe kidney diseases, and heart disease), dyslipidemia, illiterate, those with severe food compulsion at baseline (based on Binge Eating Scale) | Intervention: Snacking vs No Snacking (hypocaloric); Snacking: a hypocaloric diet divided into breakfast (15% TEE), snack (5-10% TEE), lunch (25% TEE), snack (5-10% TEE), dinner (25% TEE) and evening snack (5-10% TEE).; No Snacking: a hypocaloric diet divided into breakfast (20-25% TEE), lunch (35-40% TEE), and dinner (35-40% TEE).; The diets had the same macronutrient distribution. Diets were reduced 500-1000 kcal/d to obtain body weight reduction of 2-4 kg/mo. Breakfast, lunch and dinner were defined to provide more than 15% of the TEE and the snacks provided less than 15% of the TEE.; Duration: 12wk; Compliance: Self-reported dietary adherence: NS difference between groups; percentage (~75%) remained similar throughout intervention period; Outcomes and assessment methods:; - At baseline, 12wk; - Energy intake measured from self-reported food records that were conducted at three periodic visits during the 12wk intervention | [underlined: Total daily enerqv intake (kcal)], Marqinal mean (SD); Within group: baseline, 12wk; No Snacking: 1973.91 (86.73), 1530.00 (104.88), p=0.0106; Snacking: 1892.13 (79.65), 1292.06 (111.34). p=0.001; Between groups: p=0.888 at baseline p=0.544 at 12wk; [underlined: Change in enerqv intake (kcal) from baseline to 12wk], Marginal mean (SD); No Snacking: ~356.84 (157.58); Snacking:-733.19 (171.07); p=0.216 | Limitations:; - Methods for concealment NR; - Concerns with deviations from intended intervention; - Differences in attrition; - Water/Beverages were not accounted for in exposure; Funding:; Coordenação de Aperfeiçoamento de Pessoal de Nivel Superior (CAPES)
Johnstone, 2000^38^; RCT-Crossover, UK; Baseline N=8, Analylic N=8 (Attrition: 0%); Study objective: To examine the effects of ingesting mandatory snacks v. no snacks and the composition of isoenergetically-dense snacks high in protein, fat or carbohydrate, on food intake and energy intake in eight men with ad libitum access to a diet of fixed composition; Participant characteristics at baseline: men with normal weight; - Age: 27.3 (6.4)y; - Female: 0%; - Race and/or ethnicity: NR; - Socioeconomic position: NR; - Anthropometry: Weight 76.5 (10.2)kg; - Physical activity: NR; - Smoking: All nonsmokers; - TEI: NR; - Habitual diet at baseline: NR; Excluded from study or analysis: unstable weight history, medication, smokers | Intervention: Snack (3 isoenergetic conditions) vs. No snack (NSn); High-protein snack (HP), high-carbohydrate snack (HC), and high-fat snack (HF) were provided at fixed time intervals (11:30am, 3:30pm, 7:30pm) and each provided 30% of participants estimated daily energy requirements.; Duration: 7d (≥1wk washout), each 7d intervention was preceded by 2d of a fixed, maintenance diet; Compliance: NR; Outcomes and assessment methods:; - 9d; - Participants were provided with ad libitum access to a medium-fat diet for meals (breakfast, lunch, supper), snacks, and drinks. Food was weighed before and after consumption to calculate energy intake. Energy intake was also broken down into meals (breakfast, lunch, and supper). | Ad libitum energy intake throughout the day (kcal), Mean; NSn: 3322; HP: 2796; HC: 2796; HF: 2916; p=0.007; Ad libitum energy intake (kcal) at breakfast, lunch, supper, or snacks: p=NS between groups; Total energy intake including snacks (kcal), Mean; NSn: 3322; HP: 3416; HC: 3370; HF: 3537; p=0-63 | Limitations:; - Methods for randomization and concealment NR; - No power calculation; - No preregistered data analysis plan; - Water/Beverages were not accounted for In exposure assessment; Funding:; Scottish Office; Slimming World
VanderWal, 2006^39^; RCT-Parallel, U.S.; Baseline N=80, Analytic N=41 (Attrition: 0%); Study objective: To examine whether providing a structured post-dinner snack would enhance weight loss among night snackers with obesity participating in a novel partial meal replacement program and to examine the efficacy of that program; Participant characteristics at baseline: adult night snackers with obesity; - Age: ~46y; - Female: 72%; - Race and/or ethnicity: NR; - Socioeconomic position: NR; - Anthropometry: BMI ~38 kg/m^2^ (all with obesity); - Physical activity: NR; - Smoking: NR; - TEI: ~2350 kcal/d; - Habitual diet at baseline: NR; Excluded from study or analysis: aged <18 or >65y, BMI <30 kg/m^2^, unstable 6mo weight history, did not endorse night snacking as contributing to their weight problem | Intervention: Post dinner snack (PDS) vs No snack (NSn); PDS (n=18): participants ate a standardized bowl of ready-to-eat cereal and low-fat milk 90min after supper meal; NSn (n=23): participants were given no further instructions after supper; Both groups consumed a standardized breakfast, mid-morning snack, and lunch in addition to an Individually planned supper.; Duration: 8wk; Compliance: defined as consumption of post-dinner snack and meal replacement products by the PDS group; NS difference between groups when comparing compliance; Outcomes and assessment methods:; - At baseline, 8wk; - Participants were provided with food supplies to follow the diets. Participants returned unused food products at follow-up visits that were conducted every 2wk, and this was used to calculate energy intake. | [underlined: Change in energy intake (kcal) from baseline to 8wk] Mean (SD); NSn: −3074.02 (5471.19); PDS:-982.91 (4411.26); p=NS | Limitations:; - Methods for randomization and concealment NR from intended intervention; - Differences in attrition; - Unclear if outcome assessors were aware of; - No power calculation; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; Funding:; Kellogg Company

a Abbreviations: BMI: body mass index; CON: control; d: day(s); EI: energy intake; EX: exercise; kcal: kilocalorie(s); m: meter(s); min: minute(s); MJ: megajoule; MVPA: moderate to vigorous physical activity; NB: no breakfast; NR: not reported; NS: not significant; NSn: no snack; PDS: post dinner snack; RCT: randomized controlled trial; SE: standard error; SD: standard deviation; SN: snack; TEI: total energy intake; wk: week(s); y: year(s)

Table 17 Risk of bias for randomized controlled trials examining snacking in adults and energy intake^a^

Article | Randomization | Period and carryover effects | Deviations from intended interventions (effect of assignment) | Missing outcome data | Outcome measurement | Selection of the reported result | Overall risk of bias
Bachman, 2012 ^32^ | LOW | NOT APPLICABLE | LOW | LOW | LOW | LOW | LOW
Grangeiro, 2021 ^34^ | SOME CONCERNS | NOT APPLICABLE | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS
Forslund, 2008 ^33^ | LOW | NOT APPLICABLE | HIGH | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Johnstone, 2000 ^38^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Vander Wal, 2006 ^39^ | SOME CONCERNS | NOT APPLICABLE | SOME CONCERNS | HIGH | LOW | SOME CONCERNS | HIGH

a Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898. doi:10.1136/bmj.l4898 31462531 .)