# Results

## Literature search and screening results

The literature search was conducted to identify all potentially relevant articles for 3 systematic reviews assessing frequency of meals and/or snacking and different outcomes (alignment with the Dietary Guidelines for Americans (diet quality)^†^; growth, body composition, and risk of obesity^‡^; and energy intake), however this report is specific to the outcome of energy intake. The literature search (Appendix 2) yielded 31,399 search results after the removal of duplicates (see Figure 2). Dual-screening resulted in the exclusion of 27,732 titles, 2,821 abstracts, and 704 full-texts articles. Reasons for full-text exclusion are in Appendix 3. No additional articles were identified from the manual search. The body of evidence on frequency of meals and/or snacking and energy intake included 39 articles.

- Frequency of meals and/or snacking in children and adolescents: 5 articles^1–5^
- Breakfast in adults and older adults: 26 articles^6–31^
- Number of eating occasions in adults and older adults: 6 articles^32–37^
- Snacking in adults and older adults: 5 articles^32–34,38,39^

† Palacios C, Andres A, Odoms-Young A, . Frequency of Meals and/or Snacking and Consuming a Dietary Pattern That is Aligned With the Dietary Guidelines for Americans: A Systematic Review. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review; 2025. 10.52570/NESR.DGAC2025.SR09

‡ Palacios C, Raynor HA, Anderson CAM, . Frequency of Meals and/or Snacking and Growth, Body Composition, and Risk of Obesity: A Systematic Review. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review; 2025. 10.52570/NESR.DGAC2025.SR16

Figure 2 Literature search and screen flowchart

Literature search and screen flowchart The literature search in PubMed, Embase, Cochrane, and CINAHL retrieved 31,399 records after removing duplicates. No articles were found with manual search methods. 27,732 titles, 2821 abstracts, and 704 full-texts were excluded. 142 articles were included across the 3 systematic reviews examining frequency of meals and/or snacking. Of these, 39 articles were included in the systematic review on energy intake.

## Frequency of meals and/or snacking in children and adolescents

### Description of the evidence

Five articles examined the relationship between frequency of meals and/or snacking in children and adolescents and energy intake.^1–5^ All included articles were crossover randomized trials. Included articles are summarized in Table 8, which encompasses each articles’ definition of the specific category of frequency of meals and/or snacking being assessed in. Risk of bias assessments for each article are summarized in Table 9.

#### Population

Two articles were conducted in the U.S.^1,2^ and 3 articles^3–5^ were conducted in the UK. Sample size of study groups ranged from N=11 up to N=38. All trials were conducted in children with mean ages ranging from approximately 8.5 years to 13 years. Two articles were conducted only in females^4,5^ while the other 3 included both males and females.

Two articles from the U.S. reported data on race and/or ethnicity: 83% White^2^; 76% African American, 19% White, 5% Mixed race^1^. None of the articles reported a measure of socioeconomic position. All articles included participants with varying baseline weight status, except for an article^1^ that only included children within the category of normal BMI-for-age.

#### Intervention/exposure and comparator

Three articles^1,4,5^ analyzed breakfast consumption, 1 article^3^ assessed snacking, and 1 article^2^ assessed number of eating occasions. The duration of the trials ranged from 1 day to 7 days (with a range of 2-day to 28-day washout periods).

##### Breakfast

In the 3 trials that assessed breakfast consumption, all compared those who consumed breakfast compared to those who did not consume breakfast.^1,4,5^ Kral and colleagues^1^ assessed breakfast consumption in a lab setting, looking only at single meal (with a 1-week washout period). The breakfast that was offered consisted of ready-to-eat breakfast cereal, 1% milk, banana, and orange juice. Zakrzewski-Fruer and colleagues conducted a study in the school setting and offered breakfast consisting of ready-to-eat cereal, semi-skimmed milk, and orange juice.^4^ Zakrzewski-Fruer and colleagues assessed breakfast consumption at home and the offered breakfast consisted of ready-to-eat cereal with semi-skimmed milk, orange or apple juice, and optional raisins.^5^

##### Snacking

The included trial^4^ that assessed snacking was a multi-component 1-day crossover trial with 4 conditions, all completed in a temporary lab setup within the school:

1. Control condition: no snack and no exercise
2. Snack: mid-morning snack
3. Exercise: moderate-intensity exercise
4. Snack + Exercise: mid-morning snack and moderate intensity exercise

Energy content of the offered snacks ranged from 1000-1033 kJ (239-247 kcal), carbohydrate ranged from 51-55%, protein from 11-12% and fat from 33-37%.

##### Number of eating occasions

The included trial that assessed number of eating occasions per day compared groups that consumed 2 isocaloric meal patterns, but in either 5 occasions (8am, 10am, 12pm, 2pm, 5pm) or 3 occasions (8am, 12pm, 5pm).^2^ The following foods were offered at each study visit: Cheerios®; 2% milk; banana; wheat toast; butter; cinnamon sugar; string cheese; chocolate chip granola bar; mandarin oranges; peanut butter; Premium® saltine crackers; apple juice; skim milk; Kraft® macaroni & cheese; Lit’l Smokies®; green beans; apple slices; Kool-Aid®, sugar-free; baby carrots; ranch dressing; chocolate milk, 1% fat; vanilla wafers; Hershey’s Kisses®; canned peaches; juice pack; cottage cheese, 2% fat; whole milk; breaded chicken breast tenders; barbecue sauce; mashed potatoes; whipped margarine; chicken gravy; peas; and fruit punch.

#### Outcome

Among the 3 trials that assessed breakfast consumption, energy intake was assessed on the same day that each of the breakfast interventions took place. In one of the articles, energy intake at the subsequent lunch was measured in the lab by weighing all foods and beverages before and after the meal; while energy intake throughout the rest of the day was measured using a food record filled out by parental report.^1^ In the other 2 articles, energy intake was measured by food diaries combined with digital photographs of the foods and beverages consumed.^4,5^ Energy intakes (kcal) throughout the test day were reported at lunch^1^, during the remainder of the day/post breakfast^1,4,5^, and as total daily energy intake.^1,4,5^ Additionally, Kral and colleagues^1^ also reported all three outcome timepoints as energy density (kcal per gram).

In the one trial that assessed snacking, participants were offered pizza during lunch to eat ad libitum at the lab. Energy intake from lunch was calculated by weighing the plate before and after the food was consumed.^3^

The trial that assessed number of eating occasions per day measured energy intake from an offering of ad libitum ice-cream 2 hours following the last feeding on the same day as the intervention.^2^

### Synthesis of the evidence

Five trials assessed frequency of meals and/or snacking and energy intake in children: 3 assessed breakfast, 1 assessed snacking, and 1 assessed the number of eating occasions per day.

#### Breakfast

Two out of 3 trials reported that children who consumed breakfast had higher total daily energy intakes on the day of testing compared to children who did not consume breakfast.^1,4^ The other trial reported no difference in total daily energy intake between breakfast groups.^5^

One of the trials that reported a significant difference in total daily energy intake, reported that adolescent girls who ate breakfast had lower post-breakfast energy intake compared to girls who did not eat breakfast, indicating that the calories consumed at the randomized breakfast lead to the total daily energy intake result.^4^ The other trial reported no other differences in energy intake at lunch or throughout the remainder of the day.^1^

#### Snacking

In the trial where adolescents were randomized to 4 conditions (control, mid-morning snack, exercise, or mid-morning snack and exercise), there were no between group differences in energy intake at an ad libitum lunch later that same day.^3^ There was a higher mean difference in energy intake relative to energy expenditure in those that had a mid-morning snack and moderate-intensity exercise compared to when participants only had exercise and no snack.

#### Number of eating occasions

In an energy-controlled trial, children with obesity consumed more calories from an offering of ice cream after eating 5 meals that day compared to 3 meals, whereas children with normal weight consumed fewer calories from an offering of ice cream after eating 5 meals that day compared to 3 meals.^2^

### Conclusion statement and grade

The 2025 Dietary Guidelines Advisory Committee was not able to develop a conclusion statement to answer the question, “What is the relationship between frequency of meals and/or snacking and energy intake?” based on their review of evidence in children and adolescents (Table 4). While the literature search was comprehensive, a search of the gray literature was not done, which may increase the possibility of publication bias. However, there were too few studies to thoroughly evaluate publication bias and it is unknown if the influence of publication bias contributed to the lack of articles available for inclusion in this body of evidence.

Table 4 Conclusion statement and grade for frequency of meals and/or snacking in children and adolescents and energy intake

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between frequency of meals and/or snacking in children and adolescents and energy intake because of substantial concerns with heterogeneity of exposures in a small body of evidence.
Grade | Grade Not Assignable
Body of Evidence | 5 articles: all crossover RCT
Rationale | Only a small number of articles met inclusion criteria for this review, and they varied in exposures and outcomes assessed; - 3 trials assessed breakfast consumption, 1 trial assessed snacking, and 1 trial assessed number of eating occasions.; - 3 trials assessed energy intake at subsequent eating occasions as well as total daily energy intake, while the 2 other trials only measured energy intake at a subsequent eating occasion.

## Breakfast in adults and older adults

### Description of the evidence

Twenty-six articles examined the relationship between breakfast consumption in adults and older adults and energy intake.^6–31^ Twenty-five articles^6–29,31^ included data from randomized controlled trials and 1 article^30^ reported data from a prospective cohort study. Six of the trial articles presented data from the same established trial project (Bath Breakfast Study), but examined different measures of frequency, outcomes, timepoints and/or subsets of participants.^7–12^ Seven articles from 4 unique trials were parallel-arm designs^7–9,12,19,20,23^ and 18 articles from 17 unique trials were crossover designs.^6,10,11,13–18,21,22,24–29,31^ Evidence for breakfast in adults and older adults and energy intake is summarized in Table 10, which encompasses each articles’ definition of breakfast consumption. Risk of bias assessments are summarized in Table 11 (RCT) and Table 12 (observational).

#### Population

The prospective cohort study was conducted in the U.S. in a predominantly White sample of participants (N=178; mean age 52 years; 73% female) with overweight/obesity and metabolic syndrome.^30^ The article was a secondary analysis of an RCT comparing the American Heart Association diet to a high-fiber diet.

Among trials, sample size of study groups ranged from N=10 to N=54. The majority of articles included young adult populations in their 20s.^6,13–29,31^ Six studies included adults with mean ages ranging from 35 to 44 years.^7–12^ Several trials exclusively enrolled those at high-risk for diet-related chronic disease, with 100% participants with overweight or obesity.^8,9,11,20,21,23,27,30^ Seven trials reported a mean BMI ≥25 kg/m2.^8,9,11,20,21,23,27^ The majority of the trials were conducted in the U.K.,^6–18,24,26,28^ 7 studies were conducted in the U.S.,^19–23,27,31^ 1 each in Italy and Japan.^25,29^ Multiple articles represented data from the Bath Breakfast Study, but it examined different subsets of participants.^7–12^

Information on race and/or ethnicity was not reported in 22 studies.^6–19,21,22,24–26,28,29,31^ however, 2 articles indicated participant heritage from the country of conduct (e.g., Japan and Italy).^25,29^ Three trials reported data on race and/or ethnicity: 61% Caucasian, 35% African American, 4% Other^20^; 58% Caucasian, 13% Black, 8% Asian, 8% Indian, 13% Hispanic^23^; 72% Caucasian, 22% African American, 6% Asian (88% Non-Hispanic)^27^. The majority of the articles did not report any measure of socioeconomic position.^6–17,19–21,23–28,31^ Education was only reported in 4 articles,^18,22,29,30^ 2 of which were being conducted in university students.^22,29^ One article also reported a measure of income and employment status.^30^

#### Intervention/exposure and comparator

The prospective cohort study measured breakfast consumption (defined as any food/beverage, excluding water, at the first eating episode no later than 10:00am) at baseline using three 24-hour recalls.^30^

Among trials, all articles compared breakfast consumption to no breakfast consumption. The majority of articles compared breakfast consumption to no breakfast consumption dichotomously.^6–13,15,17–19,24,27,29–31^ Nine articles examined multiple categories of breakfast consumption (compared to a group that did not eat breakfast), in which the breakfast consumption groups differed by another component, such as nutritional content (e.g., high-protein versus normal-protein^20,21^; high-carbohydrate versus high-fiber^22^; protein-based versus carbohydrate-based^23^), specific foods (bread versus muesli versus rice^25^; whole-food breakfast versus low-calorie placebo breakfast^26^), amount (20 grams versus 40 grams^28^), or physical activity level (breakfast combined with exercise or rest^14,16^). Trial duration ranged from 1 day to 12 weeks; most trials were 1 day,^6,10,11,13,14,16,17,22,26–29^ 7 trials were 1-2 weeks,^15,18,21,23–25,31^ 5 trials were 4-6 weeks,^7–9,12,19^ and 1 trial^20^ was 12 weeks.

#### Outcome

Articles were included if they examined any measure of energy intake, and therefore there was some heterogeneity in the reported outcomes. The prospective cohort study reported change in total energy intake (representing kilocalories per day) over 1 year measured from three 24-hour dietary recalls.^30^

Among trials, the majority of articles measured energy intake by weighing the food before and after consumption.^6–14,16,17,21,22,25–28,31^ Few studies used 24-hour diet records or food diaries.^15,18–20,23,24,29^ The following outcomes were reported in the included trials:

- Energy intake during an ad libitum lunch following breakfast in controlled feeding settings.^6,8,10–14,16,22,25,26,28,29^
- Energy intake at breakfast and lunch combined following breakfast in controlled feeding settings^6,10,11,14,16,22,26^
- Energy intake consumed after lunch following breakfast and lunch in controlled feeding settings^13,22,27–29,31^
- Total daily energy intake^7,9,13–15,17–25,27–29,31^

### Synthesis of the evidence

While it is useful to evaluate the extent to which breakfast skipping may influence energy intake at subsequent meals and snacks, effects of breakfast consumption on total daily energy intake are most relevant to the systematic review question. Therefore, the synthesis of trials, conclusion statements, and grading were based on the articles that included a measure of total daily energy intake. The results in the body of evidence were mixed and had many limitations. There was serious heterogeneity in the direction and the significance of the results in the included articles. Additionally, variation in participant characteristics and study methodology made the articles difficult to compare and synthesize. Duration of trials may explain some inconsistencies seen across the body of evidence, and additional long-term studies are needed.

#### Prospective cohort study

The one included prospective cohort study reported no association between baseline breakfast consumption and change in total daily energy intake over a 1-year follow-up.^30^

Some limitations noted included that the paper did not account for anthropometry, the exposure assessment method was not validated, and exposure data was only assessed at baseline leading to a concern that changes in exposure status occurred over 1-year follow-up. There was no information on non-completers and no preregistered data analysis plan.

#### Randomized controlled trials

##### Total daily energy intake

Total daily energy intake was examined in 18 trials. ^7,9,13–15,17–25,27–29,31^ While 2 of the trial articles were from the same project, they report results from different groups of participants and will be referred to as separate trials for the remainder of the synthesis.^7,9^

Nine of the 18 trials reported that those who consumed breakfast ate more total daily calories compared to those who did not consume breakfast.^7,13,14,17,19,21,22,24,29^ The duration of these trials were short (5 were 1 day;^13,14,17,22,29^ 2 were 1 week;^21,24^ 2 were 4^19^ or 6 weeks^7^). One of these trials was in participants with overweight and/or obesity.^21^ The majority of trials were in young adults, with the oldest population having a mean of 36 years.^7^ Three articles were exclusively in females^19,21,29^ and 3 were exclusively in males.^13,14,17^ Two articles included only usual breakfast skippers^19,21^ and 3 were in usual breakfast eaters.^13,19,29^ The foods that were consumed as part of the breakfast interventions varied across these articles and are reported in the summary table. Three trials did not provide food or instruct participants to eat specific breakfast foods,^7,19,24^ 4 trials provided milk and cereal-, oats-, or grain-based breakfasts,^13,14,17,22^ 1 included comparisons to both a high-protein breakfast (“egg and beef-rich”) as well as a ready-to-eat-cereal-based breakfast,^21^ and 1 article provided a breakfast of rice, ham, eggs, and salad.^29^ The majority of the outcomes were calculated using weighed food intake,^7,13,14,17,21,22^ which was the most accurate measurement of total energy intake, with only 3 studies using 24-hour recalls, food diaries, or purchased food labels and photographs.^19,24,29^

Seven of the 18 trials reported no differences in total energy intake between those who consumed breakfast compared to those who did not consume breakfast.^9,18,23,25,27,28,31^ The duration of these trials were also short, with the longest being 6 weeks,^9^ 2 were 1 day,^27,28^ and 4 were about 1 week.^18,23,25,31^ All but one of these studies were in participants in their 20s,^4^ and 2 studies were conducted in participants with overweight or obesity.^9,27^ The breakfasts that were offered varied substantially, with 4 focusing on cereal and milk or high-carbohydrate options (1 of which also offered eggs^27^),^18,25,27,28^ 1 offered high-protein options,^31^ 1 included comparisons to both a high protein and a high-carbohydrate breakfast,^23^ and 1 did not provide or instruct what foods to consume during breakfast.^9^ Three articles were exclusively in women,^23,27,28^ and 1 was exclusively in men.^25^ The majority of outcomes included weighing the foods to determine total daily energy intake,^9,25,27,28,31^ with only 2 studies incorporating other methods.^18,23^

Two out of 18 articles reported that those who consumed breakfast ate fewer total daily calories compared to those who did not consume breakfast.^15,20^ Both of these articles were longer in duration at 12 weeks and 14 weeks; however, both articles measured energy intake using 3-day food records or 24 hour recalls which were interpreted as a less accurate method compared to weighed food intakes. One article was conducted in healthy weight young women (mean age 25.5 years) who consumed breakfast regularly, while the other was in breakfast skipping young adults (mean age of 19 years) with overweight and/or obesity. The breakfasts foods provided in these two trials were different, one with whole-grain cereal with milk and the included comparisons to both a high-protein breakfast (“egg and pork-rich”) as well as a ready-to-eat-cereal-based breakfast.

##### Energy intake from subsequent meals and/or snacks

The synthesis and conclusion statements in this systematic review are focused on total daily energy intake; however, additional shorter-term energy intake outcomes were included and considered in discussions.

Energy intake during an ad libitum lunch following breakfast in controlled feeding settings: Thirteen trials (11 crossovers) examined breakfast intake in relation to energy intake after an ad libitum lunch.^6,8,10–14,16,22,25,26,28,29^ Seven trials (including 2 parallel trials) found that there was no difference in energy consumed at lunch between those who consumed a standardized breakfast compared to those who did not.^8,11,12,14,16,25,28^ Six trials found that those who consumed breakfast ate fewer calories at an ad libitum lunch compared to those who did not consume breakfast.^6,10,13,22,26,29^ None of these trials reported higher energy intake at an ad libitum lunch between those who ate breakfast compared to those who did not eat breakfast.

Energy intake at breakfast and lunch combined following breakfast in controlled feeding settings: Seven of those same trials that measured energy intake from lunch only also presented results where they summed calories from lunch with calories from breakfast.^6,10,11,14,16,22,26^ Six out of 7 trials presented results indicating that those who consumed breakfast ate more calories at lunch and breakfast compared to those who did not consume breakfast.^10,11,14,16,22,26^

Energy intake consumed after lunch following breakfast and lunch in controlled feeding settings: Six trials reported calories consumed after lunch (usually when participants had left the lab setting) – and none of those trials reported a difference in energy intake between those who consumed breakfast compared to those who did not consume breakfast.^13,22,27–29,31^

#### Summary

Overall, the results in the body of evidence were mixed and had many limitations, including the lack of diversity of the population, the different study designs and interventions as well as the diversity in energy intake assessments. These results suggest that additional standardized studies are needed in larger and longer trials to establish a conclusion statement. There was serious heterogeneity in the direction and the significance of the results in the 19 included articles that could not be explained by participant characteristics.^7,9,13–15,17–25,27–31^ Trial populations were very specific and together may not be fully representative of the adult and older adult U.S. population. All were generally young adults with selection criteria such as only including males, females, college students, those who were physically active, usual breakfast consumers, usual breakfast skippers, lean, and/or those with overweight or obesity. There was also a concern that breakfast provided in the trials may not have been reflective of usual consumption patterns and timing of eating of the U.S. population.

Study duration may be an unexplained driver of the mixed results in the trials. The majority of trials (16 of 18) had shorter durations of less than 6 weeks,^7,9,13,14,17–19,21–25,27–29,31^ many of which (9 of 16) reported that breakfast consumption led to higher total daily energy intake.^7,13,14,17,19,21,22,24,29^ However, the two trials of longer duration, 12^20^ and 14 weeks,^15^ reported results in the opposite direction leading to a concern that many of the included trials may not have been long enough to capture metabolic adjustments to consistent breakfast consumption (or non-consumption) over time. Additionally, the one observational study with a 1-year follow-up reported no association between breakfast and total daily energy intake.^30^ More studies of longer duration are needed to explain these differences in outcomes. It is likely that more research on this topic would lead to additional clarity on the inconsistencies found in this body of evidence.

### Conclusion statements and grades

The 2025 Dietary Guidelines Advisory Committee was not able to develop conclusion statements to answer the question, “What is the relationship between frequency of meals and/or snacking and energy intake?” based on their review of evidence on breakfast consumption in adults and older adults and energy intake (Table 5). While the literature search was comprehensive, a search of the gray literature was not done, which may increase the possibility of publication bias. However, this body of evidence comprised of both large and small studies, including small studies with null findings, so there are few concerns of publication bias.

Table 5 Conclusion statements and grades for breakfast consumption in adults and older adults and energy intake

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between breakfast consumption in adults and total daily energy intake because of substantial concerns with consistency and generalizability in the body of evidence. | A conclusion statement cannot be drawn about the relationship between breakfast consumption in older adults and energy intake because there is no evidence available.
Grade | Grade Not Assignable | Grade Not Assignable
Body of Evidence | 19 articles: 18 RCT, 1 prospective cohort study | 0 articles
Rationale | The available evidence contributed mixed results and had many limitations including lack of diversity of the populations, different study designs, interventions, and durations as well as diversity in energy intake assessments. | No articles met the inclusion criteria in older adults.

## Number of eating occasions in adults and older adults

### Description of the evidence

Six articles examined the relationship between number of eating occasions in adults and older adults and energy intake.^32–37^ Study designs of the included articles were 5 randomized controlled trials (3 parallel-arm trials^32–34^ and 2 crossover trials^36,37^), and 1 prospective cohort study.^35^ Evidence for number of eating occasions in adults and older adults and energy intake is summarized in Table 13, which encompasses each articles’ definition of number of eating occasions. Risk of bias assessments are summarized in Table 14 (RCT) and Table 15 (observational).

Three of the trials included in this body of evidence was also included in the snacking body of evidence.^32–34^ The analyses that are discussed are the exact same, but the exposure categories are interpreted as number of eating occasions as opposed to snacking.

#### Population

Studies were conducted in Sweden,^33,35^ U.S.,^32^ Brazil,^34^ Norway,^36^ and Greece.^37^ Sample size of study groups ranged from N=11 up to N=93.

The observational study was a secondary analysis of trial data conducted in participants who were enrolled in a 12-week weight loss intervention in postpartum women with overweight and obesity.^35^ Four out of the 5 trials were conducted in participants with overweight/obesity and/or with impaired glucose tolerance or overt type 2 diabetes.^32–34,37^ One trial was conducted in lean adults (BMI 24.0±0.6 kg/m^2^ and fat mass 24.0±0.6%).^36^

Only one article reported race and/or ethnicity or a measure of socioeconomic position, and the participants were 94% White and 98% Non-Hispanic with 88% having at least some college and 78% married. Two of the articles enrolled only females while the other 4 included both males and females.

#### Intervention/exposure

Four out of the 5 trials compared 6 meals vs. 3 meals per day,^32–34,37^ while the other compared 3 meals vs. 1 meal per day.^36^ Three were hypocaloric weight loss trials,^32–34^ and 2 were eucaloric trials.^36,37^ All trials were lab based controlled trials. The duration of the parallel trials ranged from 12 weeks to 1 year. The duration of the 2 crossover trials were 11 days (with a 2-week washout period) and 12 weeks (washout period length was not reported).

The observational study compared change in continuous eating occasions per day and measured exposure using a 4-day diet record.^35^

#### Outcome

All trials reported total daily energy intake (kcal),^32–34,36,37^ while the observational trial reported change in total daily energy intake.^35^ The assessment methods for measuring energy intake varied:

- 3-day diet record^32,34,37^
- Dietary questionnaire about past 3 months^33^
- Food diaries^36^

The observational article measured followed participants for 12 weeks from 10 to 14 weeks postpartum to post-intervention (22 to 26 weeks postpartum).^35^

### Synthesis of the evidence

#### Prospective cohort study

In an observational analysis in postpartum women with overweight and obesity undergoing a weight loss intervention, eating frequency was positively associated with an increase in total daily energy intake over 12 weeks.^35^

#### Randomized controlled trials

All 5 of the included trials reported no relationship between number of eating occasions and total daily energy intake in adults.^32–34,36,37^ All 5 trials were either weight loss trials or weight maintenance trials where the number of eating occasions and energy intake parameters was highly controlled and not generalizable to the general free-living U.S. population.

### Conclusion statement and grade

The 2025 Dietary Guidelines Advisory Committee was not able to develop a conclusion statement to answer the question, “What is the relationship between frequency of meals and/or snacking and energy intake?” based on their review of on number of eating occasions and energy intake in adults and older adults (Table 6). While the literature search was comprehensive, a search of the gray literature was not done, which may increase the possibility of publication bias. However, there were too few studies to thoroughly evaluate publication bias, and it is not likely a concern given that all but one of the 6 included articles reported null results.

Table 6 Conclusion statement and grade for number of eating occasions in adults and older adults and energy intake

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between number of eating occasions per day in adults and older adults and energy intake because of substantial concerns with generalizability in a small body of evidence.
Grade | Grade Not Assignable
Body of Evidence | 6 articles: 5 RCT, 1 prospective cohort study
Rationale | Only a small number of articles met inclusion criteria for this review and they were not generalizable to the overall U.S. population. The trials were narrowly focused on eating occasions in the context of weight loss or weight maintenance intervention trials in populations with overweight and/or obesity or in those who had previously lost weight and would not be generalizable to a free-living U.S. population.

## Snacking in adults and older adults

### Description of the evidence

Five articles examined the relationship between snacking in adults and older adults and energy intake.^32–34,38,39^ All included studies were randomized controlled trials: 4 were parallel-arm trials^32–34,39^ and 1 was a crossover trial.^38^ Evidence for snacking in adults and older adults and energy intake is summarized in Table 16, which encompasses each articles’ definition of snacking. Risk of bias assessments are summarized in Table 17.

Three of the trials included in this body of evidence was also included in the number of eating occasions body of evidence.^32–34^ The analyses that are discussed are the exact same, but the exposure categories are interpreted as snacking as opposed to number of eating occasions.

#### Population

Studies were conducted in the U.S.^32,39^ UK,^38^ Brazil,^34^ and Sweden.^33^ Sample size of study groups ranged from N=8 up to N=93. The duration of the parallel trials ranged from 8 weeks to 1 year. The duration of the crossover trial was 7 days (with a ≥1 week washout period).^38^

Only one article reported race and/or ethnicity or a measure of socioeconomic position, and the participants were 94% White and 6% Black (98% Non-Hispanic) with 88% having at least some college and 78% married.^32^ Four out of the 5 trials were conducted in participants with overweight/obesity,^34^ one of which enrolled only females.^34^ The other trial enrolled only males who were with normal weight.^38^

#### Intervention/exposure and comparator

Three out of the 5 trials were hypocaloric weight loss trials and compared 3 snacks and 3 meals per day compared to only 3 meals per day.^32–34,37^ The other two trials had varied snacking exposures including a crossover trial that compared 3 isoenergetically-dense snacks high in protein, fat or carbohydrate to no snacking,^38^ and the other that compared having a post-dinner snack compared to no intervention.^39^

#### Outcome

All trials reported total daily energy intake (kcal).^32–34,38,39^ The assessment methods for measuring energy intake varied:

- 3 day diet record,^32,34^
- Dietary questionnaire about past 3 months,^33^
- Provided food was returned and used to calculate energy intake.^38,39^ Food was weighed in one article in a lab-based setting,^38^ and method for calculation was not reported in the other.^39^

### Synthesis of the evidence

All 5 of the included trials reported no relationship between snacking and total daily energy intake in adults.^32–34,38,39^ Four out of 5 of the trials were weight loss trials where snacking and energy intake parameters were highly controlled and not generalizable to the general free-living U.S. population.^32–34,39^

### Conclusion statement and grade

The 2025 Dietary Guidelines Advisory Committee was not able to develop a conclusion statement to answer the question, “What is the relationship between frequency of meals and/or snacking and energy intake?” based on their review of evidence on snacking and energy intake in adults and older adults (Table 7). While the literature search was comprehensive, a search of the gray literature was not done, which may increase the possibility of publication bias. However, there were too few studies to thoroughly evaluate publication bias, and it is not likely a concern given that all 5 included articles reported null results.

Table 7 Conclusion statement and grade for snacking in adults and older adults and energy intake

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between snacking in adults and older adults and energy intake because of substantial concerns with generalizability in the body of evidence.
Grade | Grade Not Assignable
Body of Evidence | 5 articles: all RCT
Rationale | There is not enough evidence available to answer this question and the evidence that is available is not generalizable to the overall U.S. population. The trials were narrowly focused on snacking in the context of weight loss intervention trials in participants with overweight and/or obesity and would not be generalizable to a free-living U.S. population.