# Methods

The Committee used NESR’s methodology to conduct this systematic review. NESR’s methodology is described in detail in its methodology manual,^‡^ as well as in the Committee’s Scientific Report.^§^ This section presents an overview of the specific methods used to answer the systematic review question: What is the relationship between frequency of meals and/or snacking and energy intake?

‡ USDA Nutrition Evidence Systematic Review Branch. USDA Nutrition Evidence Systematic Review: Methodology Manual. February 2023. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://nesr.usda.gov/methodology-overview

§ 2025 Dietary Guidelines Advisory Committee. 2024. Scientific Report of the 2025 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Health and Human Services and Secretary of Agriculture. U.S. Department of Health and Human Services. 10.52570/DGAC2025

## Develop a protocol

A systematic review protocol is the plan for how NESR’s methodology will be used to conduct a specific systematic review and is established by the Committee, a priori, before any evidence is reviewed. The protocol is designed to capture the most appropriate and relevant body of evidence to answer the systematic review question. Development of the protocol involves discussion of the strengths and limitations of various methodological approaches relevant to the question, which then inform subsequent steps of the systematic review process. The protocol describes all of the methods that will be used throughout the systematic review process. Additionally, the protocol includes the following components, which are tailored to each systematic review question: the analytic framework, the inclusion and exclusion criteria, and the synthesis plan. The protocol was posted online (https://nesr.usda.gov/protocols) for the public to view and comment on.

## Develop an analytic framework

An analytic framework visually represents the overall scope of the systematic review question and depicts the contributing elements that were examined and evaluated. It presents the core elements of each systematic review question, including the Population (i.e., those who experience the intervention/exposure and/or outcome), Intervention and/or exposure (i.e., the independent variable of interest), Comparator (i.e., the alternative being compared to the intervention or exposure), and Outcome(s). The Committee identified key confounders based on their knowledge of nutrition and health research and experience as subject matter experts. Key confounders are participant characteristics, such as demographics, health status, and diet and lifestyle behaviors, and/or other factors related to both the intervention/exposure and the outcome of interest that may impact the relationships of interest. Key confounders were considered during review and evaluation of the evidence, particularly during the risk of bias assessment of non-randomized and observational studies.

Figure 1 is the analytic framework for the systematic review. The intervention or exposure of interest is the frequency of meals and/or snacking in young children, children, and adolescents (1 up to 19 years), and adults and older adults (19 years and older); frequency of meals and/or snacking included occasion-based measures such as meals (e.g., breakfast), snacking, and number of eating occasions, and were defined by individual study authors and therefore varied across studies. The comparator is a different frequency of meals and/or snacking. The outcome is energy intake in young children, children, adolescents, adults, and older adults. The key confounders are sex, age, physical activity, race and/or ethnicity, socioeconomic position, diet quality at baseline, and anthropometry in all populations; and smoking in adults and older adults.

Figure 1 Analytic framework for the systematic review question: What is the relationship between frequency of meals and/or snacking and energy intake?

Population | Intervention/exposure | Comparator | Outcome | Key confounders
Young children, children, and adolescents (1 up to 19 years) | Frequency of meals and/or snacking^*^; * Definitions varied across studies and included occasion-based measures such as meals (e.g., breakfast), snacking, and number of eating occasions. | Different frequency of meals and/or snacking | In young children, children and adolescents, adults and older adults:; - Energy intake | - Sex; - Age; - Physical activity; - Race and/or ethnicity; - Socioeconomic position; - Diet quality at baseline; - Anthropometry; - Smoking (adults, older adults)
Adults and older adults (19 years and older) | Frequency of meals and/or snacking^*^; * Definitions varied across studies and included occasion-based measures such as meals (e.g., breakfast), snacking, and number of eating occasions. | Different frequency of meals and/or snacking | In young children, children and adolescents, adults and older adults:; - Energy intake | - Sex; - Age; - Physical activity; - Race and/or ethnicity; - Socioeconomic position; - Diet quality at baseline; - Anthropometry; - Smoking (adults, older adults)

Synthesis organization:

I. Intervention/exposure: Meals (e.g., breakfast); Snacking; Number of eating occasions
  a. Population: Young children; Children; Adolescents; Adults; Older adults
    i. Outcome: Energy intake

## Develop inclusion and exclusion criteria

The inclusion and exclusion criteria provide an objective, consistent, and transparent framework for determining which articles to include in the systematic review (Table 2). These criteria ensure that the most relevant and appropriate body of evidence is identified for the systematic review question, and that the evidence reviewed is:^*^

- Applicable to the U.S. population of interest
- Relevant to Federal public health nutrition policies and programs
- Rigorous from a scientific perspective

* USDA Nutrition Evidence Systematic Review Branch. USDA Nutrition Evidence Systematic Review: Methodology Manual. February 2023. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://nesr.usda.gov/methodology-overview

Table 2 Inclusion and exclusion criteria

Category | Inclusion Criteria | Exclusion Criteria
Study design | - Randomized controlled trials; - Non-randomized controlled trials^†^; † Including quasi-experimental and controlled before-and-after studies; - Prospective cohort studies; - Retrospective cohort studies; - Nested case-control studies | - Uncontrolled trials^‡^; ‡ Including uncontrolled before-and-after studies; - Case-control studies; - Cross-sectional studies; - Ecological studies; - Narrative reviews; - Systematic reviews; - Meta-analyses; - Modeling and simulation studies
Publication date | - January 2000 - May 2023 | - Before January 2000, after May 2023
Population: Study participants | - Human | - Non-human
Population: Life stage | - At intervention or exposure and outcome:; ○ Young children (12 up to 24 months); ○ Children and adolescents (2 up to 19 years); ○ Adults and older adults (19 years and older); ○ Individuals during pregnancy; ○ Individuals during postpartum | - At intervention or exposure and outcome:; ○ Infants (birth up to 12 months)
Population: Health status | - Studies that [underlined: exclusively] enroll participants not diagnosed with a disease^*^; * Studies that enroll participants who are at risk for chronic disease were included; - Studies that enroll [underlined: some] participants:; ○ diagnosed with a disease;; ○ diagnosed with a disorder that affects feeding/eating or growth (e.g., autism spectrum disorder, attention-deficit/hyperactivity disorder, eating disorders);; ○ with severe undernutrition, failure to thrive/underweight, stunting, or wasting;; ○ receiving pharmacotherapy to treat obesity;; ○ pre- or post-bariatric surgery;; ○ and/or hospitalized for an illness, injury, or surgery | - Studies that [underlined: exclusively] enroll participants:; ○ diagnosed with a disease;^†^; † Studies that exclusively enroll participants with obesity were included; ○ diagnosed with a disorder that affects feeding/eating or growth (e.g., autism spectrum disorder, attention-deficit/hyperactivity disorder, eating disorders);; ○ with severe undernutrition, failure to thrive/underweight, stunting, or wasting;; ○ receiving pharmacotherapy to treat obesity;; ○ pre- or post-bariatric surgery;; ○ and/or hospitalized for an illness, injury, or surgery^‡^; ‡ Studies that exclusively enroll participants post-cesarean section were included
Intervention/Exposure | - Frequency of meals and/or snacking. Definitions will vary across studies and include occasion-based measures such as:; ○ Meals (e.g., breakfast); ○ Snacking; ○ Number of eating occasions; - Multi-component intervention in which the isolated effect of the intervention of interest on the outcome(s) of interest is provided or can be determined despite multiple components | - Studies that only examine frequency of intake of a single food, beverage or category of foods and/or beverages (e.g., frequency of cereal consumption, frequency of dairy consumption, frequency of snack foods); - Multi-component intervention in which the isolated effect of the intervention of interest on the outcome(s) of interest is not provided or cannot be determined due to multiple components
Comparator | - Different frequency of meals and/or snacking | - N/A
Outcome(s) | - Energy Intake | - N/A
Publication status | - Peer-reviewed articles published in research journals | - Non-peer-reviewed articles, unpublished data or manuscripts, pre-prints, reports, editorials, retracted articles, and conference abstracts or proceedings
Language | - Published in English | - Not published in English
Country^*^; * The classification of countries on the Human Development Index (HDI) is based on the UN Development Program Human Development Report Office (http://hdr.undp.org/en/data) for the year the study intervention occurred or data were collected. If the study does not report the year(s) in which the intervention/exposure data were collected, the HDI classification for the year of publication is applied. Studies conducted prior to 1990 are classified based on 1990 HDI classifications. If the year is more recent than the available HDI values, then the most recent HDI classifications are used. If a country is not listed in the HDI, then the current country classification from the World Bank is used (The World Bank Country and Lending Groups, available from: https://datahelpdesk.worldbank.org/knowledgebase/articles/906519-world-country-and-lending-groups) | - Studies conducted in countries classified as high or very high on the Human Development Index the year(s) the intervention/exposure data were collected | - Studies conducted in countries classified as medium or low on the Human Development Index the year(s) the intervention/exposure data were collected

## Search for and screen studies

NESR librarians, in collaboration with NESR analysts and the Committee, used the analytic framework and inclusion and exclusion criteria to develop a comprehensive literature search strategy. The literature search strategy included selecting and searching the appropriate bibliographic databases, translating search using syntax appropriate for the databases being searched, and employing search refinements, such as search filters. The full literature search is documented in Appendix 2.

The results of all electronic database searches, after removal of duplicates, were screened independently by 2 NESR analysts using a step-wise process by reviewing titles, abstracts, and full-texts to determine which articles meet the inclusion criteria. Manual searching was conducted to find peer-reviewed published articles not identified through the electronic database search. These articles were also screened independently by two NESR analysts at the abstract and full-text levels.

## Extract data and assess the risk of bias

NESR analysts extracted all essential data from each included article to describe key characteristics of the available evidence, such as the author, publication year, cohort/trial name, study design, population life stage at intervention/exposure and outcome, intervention/exposure and outcome assessment methods, and outcomes. One NESR analyst extracted the data and a second NESR analyst reviewed the extracted data for accuracy. Each article included in the systematic review underwent a formal risk of bias assessment, with 2 NESR analysts independently completing the risk of bias assessment using the tool that is appropriate for the study design.^†^,^‡^,^§^

† Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898.doi: 10.1136/bmj.l4898 31462531

‡ Sterne JAC, Hernán MA, Reeves BC, . ROBINS-I: a tool for assessing risk of bias in non-randomized studies of interventions. BMJ 2016; 355; i4919; doi: 10.1136/bmj.i4919 27733354

§ Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602.

## Synthesize the evidence

The Committee described, compared, and combined the evidence from all included studies to answer the systematic review question.^**^ Synthesis of the body of evidence involved identifying overarching themes or key concepts from the findings, identifying and explaining similarities and differences between studies, and determining whether certain factors impact the relationships being examined, which includes potential causes of heterogeneity across all included evidence.

** USDA Nutrition Evidence Systematic Review Branch. USDA Nutrition Evidence Systematic Review: Methodology Manual. February 2023. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://nesr.usda.gov/methodology-overview

Extracted data and risk of bias assessments for all included studies were tabulated to visually display results and facilitate synthesis. During synthesis, the Committee considered the effect direction, magnitude, and statistical significance of the results reported across the articles included in the body of evidence. The evidence was synthesized qualitatively without meta-analysis of effect estimates, statistical pooling or conversion of data, or quantitative tests of heterogeneity.

The synthesis plan for this review was designed with the end-use in mind, to inform the Committee’s advice to HHS and USDA regarding dietary guidance across life stages. The first level of synthesis organization was intended to be by frequency of meals and/or snacking categories (e.g., breakfast, snacking, number of eating occasions etc.). Then, within each of the frequency categories, the evidence was to be organized by similar populations based on the available evidence. Finally, the next level of organization was going to be according to similar outcomes. Based on the evidence that was included, we were not able to synthesize by every intended level of organization. When it was not possible to synthesize as planned, the overall category of frequency of meals and/or snacking was used. The organization that is presented in the report below are those where there was adequate evidence available.

## Develop conclusion statements and grade the evidence

After the Committee synthesized the body of evidence, they drafted a conclusion statements. A conclusion statement is one or more summary statements carefully constructed to answer the systematic review question. Each conclusion statement reflects the evidence reviewed, as outlined in the analytic framework (e.g., PICO elements) and synthesis plan, and does not take evidence from other sources into consideration. Conclusion statements do not draw implications and should not be interpreted as dietary guidance. The Committee reviewed, discussed, and revised the conclusion statement until they reached agreement on wording that accurately reflected the body of evidence.

The Committee then graded the strength of the evidence underlying each conclusion statement. They did this using NESR’s predefined criteria, based on 5 grading elements: consistency, precision, risk of bias, directness and generalizability of the evidence. Study design and publication bias were also considered.^*^

- [underlined: Consistency]: Consistency considers the degree of similarity in the direction and magnitude of effect across the body of evidence. This element also considers whether differences across the results can be explained by variations in study designs and methods.
- [underlined: Precision]: Precision considers the degree of certainty around an effect estimate for a given outcome. This element considers measures of variability, such as the width and range of confidence intervals, the number of studies, and sample sizes, within and across studies.
- [underlined: Risk of bias]: Risk of bias considers the likelihood that systematic errors resulting from the design and conduct of the studies could have impacted the accuracy of the reported results across the body of evidence.
- [underlined: Directness]: Directness considers the extent to which studies are designed to directly examine the relationship among the interventions/exposures, comparators, and outcome(s) of primary interest in the systematic review question.
- [underlined: Generalizability]: Generalizability considers whether the study participants, interventions and/or exposures, comparators, and outcomes examined in the body of evidence are applicable to the U.S. population of interest for the review.

* Spill MK, English LK, Raghavan R, . Perspective: USDA Nutrition Evidence Systematic Review Methodology: Grading the Strength of Evidence in Nutrition- and Public Health-Related Systematic Reviews. Adv Nutr. 2022 Aug 1;13(4):982–991. doi: 10.1093/advances/nmab147 34918032

The Committee assigned a grade to each conclusion statement (i.e., strong, moderate, limited, or grade not assignable). The grade communicates the strength of the evidence supporting a specific conclusion statement to decision makers and stakeholders. A conclusion statement can receive a grade of Strong, Moderate, or Limited, and if insufficient or no evidence is available to answer a systematic review question, then no grade is assigned (i.e., Grade Not Assignable) (Table 3). The overall grade is not based on a predefined formula for scoring or tallying ratings of each element. Rather, each overall grade reflects the expert group’s thorough consideration of all of the grading elements, as they each relate to the specific nuances of the body of evidence under review.

Table 3 Definitions of NESR grades

Grade | Definition
Strong | The conclusion statement is based on a strong body of evidence as assessed by consistency, precision, risk of bias, directness, and generalizability. The level of certainty in the conclusion is strong, such that if new evidence emerges, modifications to the conclusion are unlikely to be required.
Moderate | The conclusion statement is based on a moderate body of evidence as assessed by consistency, precision, risk of bias, directness, and generalizability. The level of certainty in the conclusion is moderate, such that if new evidence emerges, modifications to the conclusion may be required.
Limited | The conclusion statement is based on a limited body of evidence as assessed by consistency, precision, risk of bias, directness, and generalizability. The level of certainty in the conclusion is limited, such that if new evidence emerges, modifications to the conclusion are likely to be required.
Grade Not Assignable | A conclusion statement cannot be drawn due to either a lack of evidence, or evidence that has severe limitations related to consistency, precision, risk of bias, directness, and generalizability.

## Recommend future research

The Committee identified and documented research gaps and methodological limitations throughout the systematic review process. These gaps and limitations are used to develop research recommendations that describe the research, data, and methodological advances that are needed to strengthen the body of evidence on a particular topic. Rationales for the necessity of additional or stronger research are also provided with the research recommendations.

## Peer review

This systematic review underwent external peer review in a process coordinated by staff from the National Institutes of Health (NIH). NIH staff identified potential peer reviewers through outreach to a variety of professional organizations to select academic reviewers from U.S. colleges and universities across the country with a doctorate degree, including MDs, and expertise specific to the questions being reviewed. All peer reviewers were external to the Dietary Guidelines process, and therefore, current Committee members or Federal staff who supported the Committee or the development of the Dietary Guidelines were not eligible to serve as peer reviewers.

The peer review process was anonymous and confidential in that the peer reviewers were not identified to the Committee members or NESR staff, and in turn, the reviewers were asked not to share or discuss the review with anyone. Peer reviewers were made aware that per USDA, Food and Nutrition Service (FNS) agency policy, all peer reviewer comments would be summarized and made public, but comments would not be attributed to a specific reviewer.

Peer review occurred after draft conclusion statements were discussed by the full Committee at its third, fourth, fifth, and sixth public meetings. NIH staff assigned and distributed the reviews to at least 2 peer reviewers based on area of expertise. Following peer review, the Committee reviewed and discussed comments and made revisions to the systematic review, as needed, based on the discussion.

## Health equity considerations

The Committee was charged by HHS and USDA to review all scientific questions with a health equity lens to ensure that the next edition of the Dietary Guidelines is relevant to people with diverse racial, ethnic, socioeconomic, and cultural backgrounds. The Committee made a number of health equity considerations throughout the NESR systematic review process. The Committee’s Scientific Report^*^ includes a more detailed discussion of their approach to applying a health equity lens to their review of evidence, but examples include consideration of key confounders relevant to health equity and assessment of generalizability of the evidence.

* 2025 Dietary Guidelines Advisory Committee. 2024. Scientific Report of the 2025 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Health and Human Services and Secretary of Agriculture. U.S. Department of Health and Human Services. 10.52570/DGAC2025