# Plain language summary

### What is the question?

The question is: What is the relationship between frequency of meals and/or snacking and energy intake? The populations of interest for this question include children and adolescents (1 up to 19 years), and adults and older adults (19 years and older).

### Why was this question asked?

This systematic review was conducted by the 2025 Dietary Guidelines Advisory Committee as part of the process to develop the Dietary Guidelines for Americans, 2025-2030.

### How was this question answered?

The Committee conducted a systematic review to answer this question with support from the USDA Nutrition Evidence Systematic Review team.

### What is the answer to the question?

#### Frequency of meals and/or snacking in children and adolescents

- A conclusion statement cannot be drawn about the relationship between frequency of meals and/or snacking in children and adolescents and energy intake because of substantial concerns with heterogeneity of exposures in a small body of evidence.

#### Breakfast in adults and older adults

- A conclusion statement cannot be drawn about the relationship between breakfast consumption in adults and total daily energy intake because of substantial concerns with consistency and generalizability in the body of evidence.
- A conclusion statement cannot be drawn about the relationship between breakfast consumption in older adults and energy intake because there is no evidence available.

#### Number of eating occasions in adults and older adults

- A conclusion statement cannot be drawn about the relationship between number of eating occasions per day in adults and older adults and energy intake because of substantial concerns with generalizability in a small body of evidence.

#### Snacking in adults and older adults

- A conclusion statement cannot be drawn about the relationship between snacking in adults and older adults and energy intake because of substantial concerns with generalizability in the body of evidence.

### How up-to-date is this systematic review?

Conclusion statements from this review are based on articles published between January 2000 and May 2023.