# Appendix 2 Literature search strategy

[underlined: Database: PubMed]

Provider: U.S. National Library of Medicine

Date(s) Searched: May 15, 2023

Dates Covered: January 1, 2000 – May 15, 2023

Table A 2 Search for PubMed

Search # | Concept | String
#1 | Frequency of meals and snacking | ((“Feeding Behavior”[Mesh:noexp] OR “Meals”[Mesh] OR meal*[tiab] OR lunch[tiab] OR dinner[tiab] OR eating[tiab]) AND (frequenc*[tiab] OR time*[tiab] OR timing*[tiab] OR skip*[tiab] OR episode*[tiab] OR occasion*[tiab])) OR “Breakfast”[MeSH] OR breakfast[tiab] OR “morning meal”[tiab] OR “Snacks”[MeSH] OR snack*[tiab] OR “daily meal*”[tiab]
#2 | Growth, body composition, and risk of obesity | “Adipose Tissue”[Mesh] OR “Body Composition”[Mesh] OR “Body Weights and Measures”[MeSH:NoExp] OR “Body Fat Distribution”[Mesh] OR “Body Mass Index”[Mesh] OR “Body Size”[Mesh] OR “Skinfold Thickness”[Mesh] OR “Waist-Hip Ratio”[Mesh] OR “Overnutrition”[Mesh] OR “Growth”[Mesh:NoExp] OR anthropometr*[tiab] OR body fat[tiab] OR fat mass[tiab] OR fat free mass[tiab] OR lean mass[tiab] OR obese[tiab] OR obesity[tiab] OR underweight[tiab] OR ove rweight[tiab] OR weight status[tiab] OR head circumference[tiab] OR arm circumference[tiab] OR calf circumference[tiab] OR neck circumference[tiab] OR thigh circumference[tiab] OR waist circumference[tiab] OR waist to hip ratio[tiab] OR waist hip ratio[tiab] OR body mass index[tiab] OR BMI[tiab] OR adipos*[tiab] OR body weight[tiab] OR body height[tiab] OR body size[tiab] OR body composition[tiab] OR overnutrition[tiab] OR wasting[tiab] OR healthy weight[tiab] OR skin fold[tiab] OR skin folds[tiab] OR skinfold[tiab] OR skinfolds[tiab]; OR “Weight Reduction Programs”[Mesh] OR “Body-Weight Trajectory “[Mesh] OR “Weight Gain”[MeSH] OR “Weight Loss”[MeSH:NoExp] OR “Diet. Reducing”[Mesh] OR weight gain*[tiab] OR diet reduc*[tiab] OR weight cycling[tiab] OR weight decreas*[tiab] OR weight watch*[tiab] OR weight control*[tiab] OR weight retention[tiab] OR weight management[tiab] OR “maintain weight”[tiab:~4] OR “maintains weight”[tiab:~4] OR “maintaining weight”[tiab:~4] OR “maintained weight”[tiab:~4] OR “weight maintenance”[tiab:~4] OR “reduce weight”[tiab:~4] OR “reduces weight”[tiab:~4] OR “reducing weight”[tiab:~4] OR “reduced weight”[tiab:~4] OR “weight reduction”[tiab:~4] OR “lose weight”[tiab:~4] OR “loses weight”[tiab:~4] OR “losing weight”[tiab:~4] OR “lost weight”[tiab:-4] OR “weight loss”[tiab:-4] OR “change weight”[tiab:~4] OR “changes weight”[tiab:~4] OR “changing weight”[tiab:~4] OR “changed weight”[tiab:~4]; OR “Growth Charts”[Mesh] OR growth chart*[tiab]OR stunting[tiab] OR stunted[tiab] OR weight for height[tiab] OR stature for age[tiab] OR weight for age[tiab] OR height for age[tiab] OR length for age[tiab] OR weight for length[tiab] OR failure to thrive[tiab]
#3 | Diet quality | “Guideline Adherence”[Mesh] OR HEI[tiab] OR “healthy eating index”[tiab] OR “dietary guideline*”[tiab] OR “nutrition guideline*”[tiab] OR “nutritional guideline*”[tiab] OR “dietary recommendation*”[tiab] OR “dietary consumption”[tiab] OR “diet score*”[tiab] OR “diet index*”[tiab] OR “diet indices”[tiab] OR “dietary index*”[tiab] OR “dietary indices”[tiab] OR “food score*”[tiab] OR “dietary pattern*”[tiab] OR “diet pattern*”[tiab] OR “eating pattern*”[tiab] OR “food pattern*”[tiab] OR “diet quality”[tiab] OR “dietary quality”[tiab] OR “Healthy diet”’[tiab] OR kidmed[tiab] OR MedDietScore[tiab]
#4 | Energy intake | “Energy lntake”[MeSH] OR “energy intake”[tiab] OR “calorie intake”[tiab] OR “caloric intake”[tiab] OR “total energy”[tiab] OR “total calorie*”[tiab] OR “total caloric*”[tiab] OR “energy consum*”[tiab] OR “calorie consum*”[tiab] OR “caloric consum*”[tiab]
#5 | | #1 AND (#2 OR #3 OR #4)
#6 | Limits | #5 NOT (“Animals”[Mesh] NOT (“Animals”[Mesh] AND “Humans”[Mesh])); NOT (editorial[ptyp] OR comment[ptyp] OR commentary[tiab] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic review[ptyp] OR systematic review[ti] OR meta-analysis[ptyp] OR meta-analysis[ti] OR meta-analyses[ti] OR protocol[ti] OR retracted publication[ptyp] OR retraction of publication[ptyp] OR retraction of publication[tiab] OR retraction notice[ti] OR “retracted publication”[ti] OR “Congress”[Publication Type] OR “Consensus Development Conference”[Publication Type] OR “conference abstract*”[tiab] OR “conference proceeding*”[tiab] OR “conference paper*”[tiab] OR “practice guideline”[ptyp] OR “practice guideline”[ti]); Filters applied: English, from 2000/1/1 - 3000/12/12.

[underlined: Database: Embase]

Provider: Elsevier

Date(s) Searched: May 15, 2023

Dates Covered: January 1, 2000 – May 15, 2023

Table A 3 Search for Embase

Search # | Concept | String
#1 | Frequency of meals and snacking | (‘feeding behavior’/de OR ‘mean/exp OR meal*:ab,ti OR lunch:ab,ti OR dinner:ab,ti OR eating:ab,ti) AND (frequenc*:ab,ti OR time*:ab,ti OR timing*:ab,ti OR skip*:ab,ti OR episode*:ab,ti OR occasion*:ab,ti) OR ‘meal skipping’/exp OR breakfast:ab,ti OR ‘morning meal’;ab,ti OR snack*:ab,ti OR ‘daily meal*’;ab,ti
#2 | Growth, body composition, and risk of obesity | ‘adipose tissue’/exp OR ‘body composition’/exp OR ‘anthropometry’/de OR ‘body mass’/exp OR ‘anthropometric parameters’/exp OR ‘skinfold thickness’/exp OR ‘overnutrition’/exp OR ‘growth’/de OR ‘anthropometr*’;ab,ti OR ‘body fat’;ab,ti OR ‘fat mass’;ab,ti OR ‘fat free mass’;ab,ti OR ‘lean mass’;ab,ti OR ‘obese’;ab,ti OR ‘obesity’;ab,ti OR ‘underweight’;ab,ti OR ‘overweight’;ab,ti OR ‘weight status’;ab,ti OR ‘head circumference’;ab.ti OR ‘arm circumference’;ab,ti OR ‘calf circumference’;ab,ti OR ‘neck circumference’;ab,ti OR ‘thigh circumference’;ab,ti OR ‘waist circumference’;ab,ti OR ‘waist to hip ratio’;ab,ti OR ‘waist hip ratio’;ab,ti OR ‘body mass index’;ab,ti OR ‘BMI:ab,ti OR ‘adipos*’;ab,ti OR ‘body weight’;ab,ti OR ‘body height’;ab,ti OR ‘body size’;ab,ti OR ‘body composition’;ab.ti OR ‘overnutrition’;ab,ti OR ‘wasting’;ab,ti OR ‘healthy weight’;ab,ti OR ‘skin fold*’;ab,ti OR’skinfold*’;ab,ti; OR ‘body weight management’/exp OR ‘body weight change’/exp OR ‘weight gain*’;ab,ti OR ‘diet reduc*’;ab,ti OR ‘weight cycling’;ab,ti OR ‘weight watch*’;ab,ti OR ‘weight control*’;ab,ti OR ‘weight retention’;ab,ti OR ‘weight management’;ab,ti OR (weight NEAR/4 (decreas* OR gain* OR maint* OR reduc* OR loss* OR chang*)):ab,ti; OR ‘weight chart’/exp OR ‘growth chart*’;ab,ti OR stunting:ab,ti OR stunted:ab,ti OR ‘weight for height’;ab,ti OR ‘stature for age’;ab,ti OR ‘weight for age’;ab,ti OR ‘height for age’;ab,ti OR ‘length for age’;ab,ti OR ‘weight for length’;ab,ti OR ‘failure to thrive’;ab,ti
#3 | Diet duality | ‘healthy eating index’/exp OR HEI:ab,ti OR ‘healthy eating index’;ab,ti OR ‘dietary guideline*’;ab,ti OR ‘nutrition guideline*’;ab,ti OR ‘nutritional guideline*’;ab,ti OR ‘dietary recommendation*’;ab,ti OR ‘dietary consumption’;ab,ti OR ‘diet score*’;ab,ti OR ‘diet index*’;ab,ti OR ‘diet indices’;ab,ti OR ‘dietary index*’;ab,ti OR ‘dietary indices’;ab,ti OR ‘food score*’;ab,ti OR ‘dietary pattern*’;ab,ti OR ‘diet pattern*’;ab,ti OR ‘eating pattern*’;ab,ti OR ‘food pattern”;ab,ti OR ‘diet quality’;ab,ti OR ‘dietary quality’;ab,ti OR ‘Healthy diet”:ab,ti
#4 | Energy intake | ‘caloric intake’/exp OR ‘energy intake’;ab,ti OR ‘calorie intake’;ab,ti OR ‘caloric intake’;ab,ti OR ‘total energy’;ab,ti OR ‘total calorie*’;ab,ti OR ‘total calohc*’;ab,ti OR ‘energy consum*’;ab,ti OR ‘calorie consum*’;ab,ti OR ‘caloric consum*’;ab,ti
#5 | | #1 AND (#2 OR #3 OR #4)
#6 | Limits | #5 AND ([article]/lim OR [article in press]/lim) NOT ([animals]/lim NOT ([animals]/lim AND [humans]/lim)) AND [english]/lim NOT ([conference abstract]/lim OR [conference paper]/lim OR [conference review]/lim OR [editorial]/lim OR [erratum]/lim OR [letter]/lim OR [note]/lim OR ‘retraction of publication’;ab,ti OR ‘retraction notice’;ti OR ‘retracted publication’;ab,ti OR [review]/lim OR [systematic review]/lim OR [meta analysis]/lim OR ‘practice guideline’;ti OR ‘protocol’;ti) AND [2000-2023]/py

[underlined: Database: Cochrane Central Register of Controlled Trials (CENTRAL)]

Provider: John Wiley & Sons

Date(s) Searched: May 15, 2023

Dates Covered: January 1, 2000 – May 15, 2023

Table A 4 Search for Cochrane CENTRAL

Search # | Concept | String
#1 | Frequency of meals and snacking | (([mh ^“Feeding Behavior”] OR [mh “Meals”] OR (meal* OR lunch OR dinner OR eating):ti,ab,kw) AND (frequenc* OR time* OR timing* OR skip* OR episode* OR occasion*):ti,ab,kw) OR [mh “Breakfast”] OR [mh “Snacks”] OR (breakfast OR “morning meal” OR snack* OR “daily meal*”):ti,ab,kw
#2 | Growth, body composition, and risk of obesity | ([mh “Adipose Tissue”] OR [mh “Body Composition”] OR [mh ^“Body Weights and Measures”] OR [mh “Body Fat Distribution”] OR [mh “Body Mass Index”] OR [mh “Body Size”] OR [mh “Skinfold Thickness”] OR [mh “Waist-Hip Ratio”] OR [mh Overnutrition] OR [mh ^Growth]; OR anthropometr* OR “body fat” OR “fat mass” OR “fat free mass” OR “lean mass” OR obese OR obesity OR underweight OR overweight OR “weight status” OR “head circumference” OR “arm circumference” OR “calf circumference” OR “neck circumference” OR “thigh circumference” OR “waist circumference” OR “waist to hip ratio” OR “waist hip ratio” OR “body mass index” OR BMI OR adipos* OR “body weight” OR “body height” OR “body size” OR “body composition” OR overnutrition OR wasting OR “healthy weight” OR “skin fold” OR “skin folds” OR skinfold OR skinfolds):ti,ab,kw; OR ([mh “Weight Reduction Programs”] OR [mh “Body-Weight Trajectory”] OR [mh “Weight Gain”] OR [mh “‘Weight Loss”] OR [mh “Diet, Reducing”]; OR “diet reduc*” OR “weight cycling” OR “weight watch*” OR “weight control*” OR “weight retention” OR “weight management”):ti,ab,kw; OR ((weight NEAR/4 (decreas* OR gain* OR maint* OR reduc* OR loss* OR chang*)) OR [mh “Growth Charts”]; OR “growth chart*” OR stunting OR stunted OR “weight for height” OR “stature for age” OR “weight for age” OR “height for age” OR “length for age” OR “weight for length” OR “failure to thrive”):ti,ab,kw
#3 | Diet quality | [mh “Guideline Adherence”] OR (HEI OR “healthy eating index” OR “dietary guideline” OR “dietary guidelines” OR “nutrition guideline” OR “nutrition guidelines” OR “nutritional guideline” OR “nutritional guidelines” OR “dietary recommendation” OR “dietary recommendations” OR “dietary consumption” OR “diet score” OR “diet scores” OR “diet index” OR “diet indexes” OR “diet indices” OR “dietary index” OR “dietary indexes” OR “dietary indices” OR “food score” OR “food scores” OR “dietary pattern” OR “dietary patterns” OR “diet pattern” OR “diet patterns” OR “eating pattern” OR “eating patterns” OR “food pattern” OR “food patterns” OR “diet quality” OR “dietary quality” OR “healthy diet”):ti,ab,kw
#4 | Energy intake | [mh “Energy Intake”] OR (“energy intake” OR “calorie intake” OR “caloric intake” OR “total energy” OR “total calorie*” OR “total caloric*” OR “energy consum*” OR (calorie NEXT consum*) OR (caloric NEXT consum*)):ti,ab,kw
#5 | Limits | #1 AND (#2 OR #3 OR #4); with Publication Year from 2000 to 2023, in Trials (Word variations have been searched)

[underlined: Database: CINAHL]

Provider: EBSCO

Date(s) Searched: May 15, 2023

Dates Covered: January 1, 2000 – May 15, 2023

Table A 5 Search for CINAHL

Search # | Concept | String
#1 | Frequency of meals and snacking | TI (((MH “Eating Behavior”) OR meal* OR lunch OR dinner OR eating) AND (frequenc* OR time* OR timing* OR skip* OR episode* OR occasion*)) OR AB (((MH “Eating Behavior”) OR meal* OR lunch OR dinner OR eating) AND (frequenc* OR time* OR timing* OR skip* OR episode* OR occasion*)) OR (MH “Breakfast”) OR (MH “Snacks”) OR TI (breakfast OR “morning meal”OR snack* OR “daily meal*”) OR AB (breakfast OR “morning meal”OR snack* OR “daily meal*”)
#2 | Growth, body composition, and risk of obesity | (MH “Adipose Tissue+”) OR (MH “Body Composition+”) OR (MH “Body Weights and Measures”) OR (MH “Arm Circumference”) OR (MH “Body Height”) OR (MH “Body Mass Index”) OR (MH “Body Size”) OR (MH “Body Weight+”) OR (MH “Crown-Rump Length”) OR (MH “Waist Circumference”) OR (MH “Waist-Hip Ratio”) OR (MH “Skinfold Thickness”) OR (MH “Obesity*”) OR (MH “Overnutrition”) OR (MH “Growth”); OR (TI anthropometr* OR “body fat” OR “fat mass” OR “fat free mass” OR “lean mass” OR obese OR obesity OR underweight OR overweight OR “weight status” OR “head circumference” OR “arm circumference” OR “calf circumference” OR “neck circumference” OR “thigh circumference” OR “waist circumference” OR “waist to hip ratio” OR “waist hip ratio” OR “body mass index” OR BMI OR adipos* OR “body weight” OR “body height” OR “body size” OR “body composition” OR overnutrition OR wasting OR “healthy weight” OR “skin fold” OR “skin folds” OR skinfold OR skinfolds) OR (AB anthropometr* OR “body fat” OR “fat mass” OR “fat free mass” OR “lean mass” OR obese OR obesity OR underweight OR overweight OR “weight status” OR “head circumference” OR “arm circumference” OR “calf circumference” OR “neck circumference” OR “thigh circumference” OR “waist circumference” OR “waist to hip ratio” OR “waist hip ratio” OR “body mass index” OR BMI OR adipos* OR “body weight” OR “body height” OR “body size” OR “body composition” OR overnutrition OR wasting OR “healthy weight” OR “skin fold” OR “skin folds” OR skinfold OR skinfolds); OR (MH “Weight Reduction Programs”) OR (MH “Body Weight Changes”) OR (MH “Weight Gain+”) OR (MH “Weight Loss”) OR (MH “Diet, Reducing”); OR (Tl “diet reduc*” OR “weight cycling” OR “weight watch*” OR “weight control*” OR “weight retention” OR “weight management”) OR (AB “diet reduc*” OR “weight cycling” OR “weight watch*” OR “weight control*” OR “weight retention” OR “weight management”); OR (TI (weight N4 (decreas* OR gain* OR maint* OR reduc* OR loss* OR chang*))) OR (AB (weight N4 (decreas* OR gain* OR maint* OR reduc* OR loss* OR chang*))); OR (TI “growth chart*” OR stunting OR stunted OR “weight for height” OR “stature for age” OR “weight for age” OR “height for age” OR “length for age” OR “weight for length” OR “failure to thrive”) OR (AB “growth chart*” OR stunting OR stunted OR “weight for height” OR “stature for age” OR “weight for age” OR “height for age” OR “length for age” OR “weight for length” OR “failure to thrive”)
#3 | Diet quality | (MH “Guideline Adherence”) OR TI (HEI OR “healthy eating index” OR “dietary guideline*” OR “nutrition guideline*” OR “nutritional guideline*” OR “dietary recommendation*” OR “dietary consumption” OR “diet score*” OR “diet index*” OR “diet indices” OR “dietary index*” OR “dietary indices” OR “food score*” OR “dietary pattern*” OR “diet pattern*” OR “eating pattern*” OR “food pattern*” OR “diet quality” OR “dietary quality” OR “Healthy diet” OR kidmed OR MedDietScore) OR AB (HEI OR “healthy eating index” OR “dietary guideline*” OR “nutrition guideline*” OR “nutritional guideline*” OR “dietary recommendation*” OR “dietary consumption” OR “diet score*” OR “diet index*” OR “diet indices” OR “dietary index*” OR “dietary indices” OR “food score*” OR “dietary pattern*” OR “diet pattern*” OR “eating pattern*” OR “food pattern*” OR “diet quality” OR “dietary quality” OR “Healthy diet” OR kidmed OR MedDietScore)
#4 | Energy intake | (MH “Energy Intake”) OR TI (“energy intake” OR “calorie intake” OR “caloric intake” OR “total energy” OR “total calorie*” OR “total caloric*” OR “energy consum*” OR “calorie consum*” OR “caloric consum*”) OR AB (“energy intake” OR “calorie intake” OR “caloric intake” OR “total energy” OR “total calorie*” OR “total caloric*” OR “energy consum*” OR “calorie consum*” OR “caloric consum*”)
#5 | | S1 AND (S2 OR S3 OR S4)
#6 | Limits | S5 NOT ((MH “Animals+”) OR (MH “Animal Studies”)) NOT ((MH “Literature Review”) OR (MH “Meta Analysis”) OR (MH “Systematic Review”) OR (MH “News”) OR (MH “Retracted Publication”) OR (MH “Retraction of Publication)); Limiters - Publication Year: 2000-2023; Expanders - Apply equivalent subjects; Narrow by Language: - English